# Introduction

The U.S. Department of Agriculture (USDA) develops four USDA Food Plans (the Thrifty, Low-Cost, Moderate-Cost, and Liberal Food Plans), each of which shows how a nutritious diet may be achieved at various cost levels. Each Food Plan includes a set of market baskets applicable to 1 of 15 age-sex groups. Each market basket is a selection of foods in purchasable food categories that together can be used in meals that reflect current dietary recommendations.

The Thrifty Food Plan (TFP) serves as the basis for the maximum allotment for the Supplemental Nutrition Assistance Program (SNAP), formerly known as the Food Stamp Program. The 2018 Farm Bill mandated an update to the TFP market baskets by 2022 and every five years thereafter to reflect “current prices, composition data, consumption patterns, and dietary guidance”. The importance of updating the TFP was further reiterated in Executive Order 14002 issued by President Joseph R. Biden on January 22, 2021.

To meet this mandate, the Thrifty Food Plan, 2021 (http://www.fns.usda.gov/TFP) has been updated using a rigorous scientific process. USDA’s Center for Nutrition Policy and Promotion’s (CNPP) Nutrition Evidence Systematic Review (NESR) team completed a series of rapid reviews and evidence scans as a source of information to support systematic and rigorous decisions throughout the process.

The staff at NESR specializes in conducting food- and nutrition-related systematic reviews and evidence syntheses. The NESR staff collaborated with USDA’s CNPP Nutrition and Economic Analysis Team (NEAT), who conduct the analyses to develop the USDA Food Plans, to complete a series of rapid reviews and evidence scans to address the following research questions:

1. [underlined: Rapid Review]: What is the relationship between income and prices for food items/baskets?
2. [underlined: Rapid Review]: What is the relationship between income or Federal Assistance participation/eligibility and following a dietary pattern that aligns with the Dietary Guidelines for Americans, as measured by the Healthy Eating Index (HEI)?
3. [underlined: Rapid Review]: What is the relationship between overall diet cost and following a dietary pattern that aligns with the Dietary Guidelines for Americans, as measured by the Healthy Eating Index (HEI)?
4. [underlined: Rapid Review]: What is the relationship between income and time spent on food-at-home-related activities?
5. [underlined: Evidence Scan]: What factors influence the purchase and/or consumption of at-home convenience foods? How are these foods described in the literature?

The methods for the rapid reviews and evidence scan are detailed below.