# Chapter 5 What factors influence the purchase and/or consumption of at-home convenience foods? How are these foods described in the literature?

## Specific methods to conduct the evidence scan

### Develop a protocol

The research question, “What factors influence the purchase and/or consumption of at home-convenience foods?” was addressed with an evidence scan. Similar to the rapid reviews, a protocol was developed and followed. However, results were not extracted and no risk of bias assessment was completed. The following section describes the volume and characteristics of articles that address the purchase and/or consumption of at home-convenience foods.

The analytic framework for the evidence scan examining the relationship between different factors and the purchase and/or consumption of at-home convenience foods is presented in Figure 5-a. This analytic framework visually represents the overall scope of the evidence scan question, and depicts the contributing elements that were examined and evaluated. The intervention or exposure of interest is any factor in U.S. households or populations. The comparator is a different factor or level or factor, or no comparator. The outcomes are purchase and/or consumption of at-home convenience foods in U.S. households or populations. There are no key confounders. The other factors to be considered are how at-home convenience foods are described in the literature and may impact the relationships of interest.

Figure 5-a Analytic framework for the evidence scan on the purchase/consumption of at-home convenience foods

### Search for and select studies

The following outlines any departures from the search and select studies project methods for this specific evidence scan:

- Scopus was searched instead of Web of Science because of the overwhelming number of results from Web of Science. This decision was made because the two databases cover similar topic areas and because this was an evidence scan.
- 80% of all records were single-screened at title, abstract, and full-text levels and 20% of all records were dual-screened, independently at each of these levels.
- A manual search was not completed.

NESR analysts worked jointly with NEAT staff to establish the final inclusion and exclusion criteria and literature search strategy, which are detailed in Table 5-a and Appendix 5-a, respectively.

Table 5-a Inclusion and exclusion criteria for the evidence scan on the purchase/consumption of at-home convenience foods

Category | Inclusion Criteria | Exclusion Criteria
Study design | - Any study design, including qualitative, that is not a narrative review, systematic review, or meta-analysis | - Narrative reviews; - Systematic reviews; - Meta-analyses
Intervention/exposure | - Any factor (e.g., socioeconomic status, time, knowledge, skill, household characteristics) | - N/A
Comparator | - Different factor or level of factor; - No comparator | - N/A
Outcomes | - Purchase and/or consumption of at-home convenience foods that are:; ○ Ready-to-eat; ○ Ready-to-heat; ○ Ready-to-cook/bake; ○ Other | - Purchase and/or consumption of at-home foods that do not fit into the inclusion categories; - Purchase and/or consumption of food-away-from-home, including fast-food and full-service restaurants; - Purchase and/or consumption of beverages only
Publication date | - Jan 2008 – May 2021; - Data inclusive of 2008 (e.g., 2000-2012; 2008-2009) | - Before Jan 2008, after May 2021; - Data prior to 2008 (e.g., 2000-2007; 1999-2005)
Publication status | - Articles that have been peer-reviewed; - Grey literature: reports that have not been peer-reviewed but are available from government and nongovernmental organizations | - Articles that have not been peer reviewed and are not published in peer-reviewed journals, other than reports from government and nongovernmental organizations
Language | - Articles published in English | - Articles published in languages other than English
Country | - Studies conducted in the U.S. | - Studies conducted outside the U.S.
Study participants | - Human participants/ populations | - Non-human participants (e.g., animal studies, in-vitro models)

### Extract data

NESR analysts extracted data from each included article to objectively describe the body of evidence available to inform the evidence scan. The following outlines any departures from the extract data and assess risk of bias project methods for this specific question:

- Basic data extraction occurred at the full-text screening level, and therefore 80% of the articles were extracted by 1 analyst and 20% of the articles were extracted independently by 2 analysts and compared for agreement.
- The following data elements were extracted or bucketed into categories by the NESR analysts: publication year, study design, intervention/exposure category (factor), outcome categories (level(s) of convenience, food group(s), purchase and/or consumption), and any other notes.
  ○ Level of convenience groupings used to categorize included articles:
    ▪ Ready-to-eat (RTE): foods that require no preparation before consumption
    ▪ Ready-to-heat (RTH): foods that are already cooked, but require a change in temperature before consumption.
    ▪ Ready-to-cook (RTC) or ready-to-bake (RTB): foods that are somewhat pre-prepared, but still require cooking or baking.
    ▪ Ready-to-prepare (RTP): foods which require preparation of multiple ingredients, as well as cooking or baking
      - The specific ready-to-prepare level of convenience outcome category was added during the evidence scan process as we observed how convenience foods were being described in the literature. We listed an “Other” level of convenience outcome category in original protocol to allow for this specific situation.
  ○ Food groups used to categorize included articles
    ▪ Vegetables
    ▪ Fruit
    ▪ Grains
    ▪ Proteins
    ▪ Dairy
    ▪ Snacks
    ▪ Sweets
    ▪ Multi-component foods/meals
    ▪ Other
  ○ Only factors and purchase and/or consumption outcome categories were extracted for qualitative studies. This was because the qualitative data was often not clear enough to determine the level of convenience and/or food groups.
  ○ For both qualitative and quantitative studies, factors and purchase and/or consumption categories were extracted. Level of convenience and food group(s) examined was also extracted for quantitative studies because the qualitative data was often not clear enough to determine the level of convenience and/or food groups.
- No results were extracted from the included articles
- No risk of bias assessment was completed

### Describe the evidence

NESR analysts summarized the volume and characteristics of included studies to inform the question, what factors influence the purchase and/or consumption of at home-convenience foods? The NESR analysts summarized the data using evidence tables and figures. The results of this evidence scan do not answer the question, since no results were extracted, however it describes the landscape of available evidence pertaining to this topic.

### Recommend future research

Recommendations for future research evaluating at home-convenience foods were determined based on the gaps and limitations observed during data extraction and the description of the evidence, as previously described in the project methods. Future work addressing these gaps and limitations may contribute to the body of evidence contributing to this topic.

## Results

### Literature search and screening results

The literature search yielded 12,618 search results after the removal of duplicates (see Figure 5-b). Dual-screening resulted in the exclusion of 11,911 titles, 428 abstracts, and 190 full-text articles. Reasons for full-text exclusion are in Appendix 5-b. A manual search was not conducted and all included articles were obtained through the electronic database search. The body of evidence included 89 articles:

Figure 5-b Literature search and screen flowchart for the evidence scan on the purchase/consumption of at-home convenience foods

### Description of the evidence

This evidence scan included 89 articles that examined the relationship between different factors and the purchase and/or consumption of at-home convenience foods. Sixty-five articles included cross-sectional data,^1–65^ 10 included qualitative data,^1,15,66–73^ 5 each were prospective cohort^74–78^ and uncontrolled before-and-after studies,^79–83^ and 3 each were non-RCTs^84–86^ and RCTs.^87–89^ Two articles included both cross-sectional and qualitative data.^1,15^

#### Intervention/exposure characteristics

Ten articles included qualitative data^1,15,66–73^ and 81 articles included quantitative data.^1–65,74–89^ Within each article, 1 or more factors were identified or examined in relation to purchase and/or consumption of at-home convenience foods. Factors were identified by the study participants themselves in qualitative studies, while researchers selected which factors to study in relation to at-home convenience foods in quantitative studies.

##### Qualitative studies

The most common factor identified by study participants that influenced the purchase and/or consumption of at-home convenience foods was:

- price of food,^15,68–70,73^
- time,^15,66,72,73^
- healthfulness of the food,^15,66,68^
- family preferences,^15,67^
- federal assistance program participation/eligibility (such as SNAP or WIC),^15,68^
- ease of preparation,^15,69^
- and level of satisfaction.^69,72^

The less common factors identified included:

- age,^73^
- food security,^15^
- number of people in the household,^68^
- SES factor,^68^
- knowledge/skill,^71^
- shopping frequency,^1^
- day of the week (weekend v. weekday),^72^
- and meal skipping.^72^

Figure 5-c shows the more common factors identified in qualitative studies in relation to at-home convenience foods.

Figure 5-c Qualitative study factors identified related to the purchase/consumption of at-home convenience foods

Figure showing the more common factors identified in qualitative studies in relation to at-home convenience foods. 5 articles identified price as a factor, 4 identified time, 3 identified the healthfulness of the food, and 2 each identified family preferences, federal assistance program participation/eligibility, ease, and level of satisfaction.

##### Quantitative studies

The most common factors examined in quantitative studies in relation to the purchase and/or consumption of at-home convenience foods was:

- income,^2,4,7,10,16,17,19–21,23,26,29–31,34,38,45,47,53,54,56,59,60,62,65,77,78^
- race/ethnicity,^2,7,8,10,11,14–17,19–22,24,25,31,34,37–39,43,44,53,56,65,77^
- age,^7,10,16,17,19,21,28–30,34,38,42,45,47,50,53,54,65^
- sex,^7,10,16,17,19,21,30,34,37,38,47,53,55,65^
- year (e.g., 2008, 2009, 2010),^2,29,31,35,40,41,46,49,51,59,63,64,75^
- education,^2,10,16,17,29,34,47,54,56,60,65^
- household characteristics (e.g., number of children in the household, marriage status, language spoken at home),^7,15,29,30,34,47,54,56,62,65,77^
- federal assistance program participation/eligibility,^5,18,26,27,32–34,45,62,65^
- food security,^1,9,15,30,52,53,58,61,74^
- intervention (e.g., dietary behavior change intervention, price discount intervention, in-store healthy foods promotion intervention),^79,80,82,83,85,87–89^
- price of food,^11,24,30,31,36,77,78^
- and BMI.^10,34,37,45,76^

Figure 5-d shows the more common factors examined in quantitative studies in relation to purchase/consumption of at-home convenience foods.

Figure 5-d Quantitative study factors examined related to the purchase/consumption of at-home convenience foods

This figure shows the more common factors examined in quantitative studies in relation to at-home convenience foods. 27 articles examined income as a factor, 26 examined race/ethnicity, 18 examined age, 14 examined sex, 13 examined year, 11 each examined education and household characteristics, 10 examined federal assistance program participation/eligibility, 9 examined food security, 8 examined an intervention, 7 examined price, and 5 examined BMI.

The less commonly examined factors were:

- lifestyle factors (e.g., smoking status, alcohol intake, stress/stress management, time, physical activity, breakfast consumption (yes or no), tradition/habit, shopping frequency, times cooking from scratch per day, identification as a healthy eater/cook),^3,11,16,17,19,21,24,30,34,36–38,42,74^
- SES factors (e.g., overall SES, access/distance to a store, work hours, car ownership/access, quality of the food environment),^29,34,48,57,62,65,75,86^
- personal characteristics (e.g., depressed mood, birthplace (US versus non-US), language(s) spoken, acculturation, knowledge/skill, food agency, family preferences),^7,11,13,24,36,47,74^
- food characteristics (e.g., taste, brand, quality/healthfulness of food, package size, ease of preparation),^11,24,30,36,77,84^
- location (e.g., urban versus rural/suburban, geographic region, city),^4,29,56,57,63,75^
- federal assistance program-related factors (e.g., WIC food package revisions, amount of time since receiving SNAP benefits, WIC eligibility of item, use of WICShopper app),^5,6,12,27,81^
- and other factors (e.g., store type, month of the year).^4,26,39,41,59^

#### Outcome characteristics

At-home convenience foods were categorized based on the level of convenience, the food group(s) examined, and whether purchase and/or consumption was studied. The most commonly studied (and most convenient) category was RTE foods, followed by RTH foods, RTC or RTB foods, and ending with the least commonly studied (and least convenient) category of RTP foods:

- Seventy-two articles studied RTE foods,^1–6,8,9,11,12,14–21,23–27,29–34,37–41,43–65,74,76–89^
- 45 articles studied foods that were RTH,^1,2,4,5,7,8,10,12,13,15,20,22,25–29,31–33,35–37,39–41,43–47,51,52,54,60,62,63,65,74–76,81,87–89^
- 19 articles studied RTC or RTB foods,^2,4,26,32,33,36,39–41,43,44,46,51,60,63,64,74,76,87^
- and 11 articles studied foods that were RTP.^2,4,12,20,26,33,39,40,43,44,60^

The most commonly studied foods were sweets, followed by grains, snacks, vegetables, fruit, multi-component foods/meals, proteins, dairy, and other foods that did not fit into any of the listed groupings:

- Thirty-seven articles studied at-home convenience foods that were sweets;^2,4,8,12,15,20,21,23,26,27,29,31–34,37,39–41,43,44,46,49–52,58,60,63–65,74,76,79,85–87^
- 32 articles studied grains;^6,8,12,15,17,19–21,27,30–32,39–41,43,44,46,49–51,53,55,56,61,62,65,74,77,79,83,89^
- 30 articles studied snacks;^2,4,15,20,23,26,27,29,31–34,37,39–41,43,44,46,49–52,60,63,65,74,80,82,86,87^
- 28 articles each studied vegetables,^1,2,4,5,8,12,26,28,29,31,33,38–40,43–46,59–62,65,75,79,81,87,88^
- 28 articles studied fruit,^1,2,4,5,8,16,26,28,29,31,33,38,40,43–46,60,62,63,65,75,78,79,81,85,87,88^
- 28 articles studied multi-component foods/meals;^2,4,7,10,12,20,22,25,29,32,35–37,40,41,43–47,52,60,62–64,74,76,89^
- 26 articles studied proteins;^2–4,11,14,15,24,26,29,32,33,35,39–41,43–46,49,51,62,65,76,84,87^
- 14 articles studied dairy;^6,15,32,33,39,40,43,44,46,62–65,76^
- and 13 articles studied other foods.^9,12,13,18,25,27,29,32,44,46,48,54,57^

Lastly, 59 articles examined purchase of at-home convenience foods^1–6,8,9,11,12,14,18,23,24,26,27,29–33,35,36,39–41,43,46,49,52,54,56,57,59–68,70,73,75–84,86–89^ and 38 articles examined consumption of at-home convenience foods.^1,7,10,13,15–17,19–22,24,25,28,30,34,37,38,42,44,45,47,48,50,51,53,55,58,66,67,69–74,85,86^

##### Ready-to-eat food groups

Of the RTE foods, the most common group was:

- sweets (e.g., candy, cookies, cupcakes),^2,4,8,12,15,20,21,23,26,27,29,31–34,37,39–41,43,44,46,49–52,58,60,63–65,74,76,79,85–87^
- grains (e.g., bread, cereal),^6,8,15,17,19–21,27,30–32,39–41,43,44,46,49–51,53,55,56,61,62,65,74,77,79,83,89^
- snacks (e.g., granola bars, chips, crackers),^2,4,15,20,23,26,27,29,31–34,37,39–41,43,44,46,49–52,60,63,65,74,80,82,86,87^
- fruit (e.g., canned fruit, apples, bananas),^1,2,4,5,8,16,26,29,31,33,38,40,43–46,60,62,63,65,78,79,81,85,87,88^
- vegetables (e.g., canned vegetables, bagged salad, baby carrots),^1,2,4,5,8,26,29,31,33,38,39,43–46,59–62,65,79,81,87,88^
- proteins (e.g., canned beans/tuna, peanut butter, deli meat),^2–4,11,14,15,24,26,29,32,33,39,41,43–46,49,51,62,65,76,84,87^
- dairy (e.g., yogurt, cheese),^6,15,32,33,39,40,43,44,46,62–65,76^
- other (e.g., condiments, unspecified),^9,18,25,27,29,32,44,46,48,54,57^
- and finally multi-component foods/meals.^29,32,44,46,47,63,64^

Figure 5-e shows the breakdown of RTE food groups, which was fairly mixed.

Figure 5-e Ready-to-Eat Food Groups

This figure shows the breakdown of RTE food groups. 37 articles examined RTE sweets, 31 each examined RTE grains and RTE snacks, 26 examined RTE fruit, 24 each examined RTE vegetables and proteins, 14 examined RTE dairy, 11 examined other foods that did not fit into any of the listed food groups, and 7 examined multi-component foods/meals.

##### Ready-to-heat food groups

The most common RTH group was:

- multi-component foods/meals (e.g., frozen or chilled pre-cooked meals),^2,4,7,10,12,20,22,25,29,32,35–37,40,41,43–47,52,60,62,63,74,76,89^
- vegetables (e.g., frozen vegetables),^1,2,4,5,8,12,26,28,29,31,33,39,40,43,44,46,60,65,75,81,87,88^
- fruit (e.g., frozen fruit),^1,2,4,5,8,26,28,29,31,33,43,44,46,60,75,81,87,88^
- proteins (e.g., frozen or chilled pre-cooked meats/fish),^2,4,15,26,32,33,35,39,41,43,44,46,51,76,87^
- other (e.g., sauces, broth, unspecified),^12,13,27,29,44,46,54^
- sweets (e.g., frozen cakes/pies),^26,33,43,46^
- grains (e.g., frozen pancakes/waffles, instant rice),^12,43,46^
- snacks (e.g., frozen snacks),^40,43,46^
- and ending with dairy (e.g., frozen whipped topping, cheese dip).^46^

Figure 5-f shows the breakdown of RTH food groups. Compared to the more convenient RTE food group breakdown, the share for multi-component foods/meals increased substantially and the shares for grains, snacks, sweets, and dairy decreased substantially.

Figure 5-f Ready-to-Heat Food Groups

This figure shows the breakdown of RTH food groups. 27 articles examined RTH multi-component foods/meals, 22 examined RTH vegetables, 18 examined RTH fruit, 15 examined RTH proteins, 7 examined other foods that did not fit into any of the listed food groups, 4 examined RTH sweets, 3 each examined RTH grains and snacks, and 1 examined RTH dairy.

##### Ready-to-cook and ready-to-bake food groups

For the RTC/RTB foods, the most common category became:

- proteins (e.g., processed meat),^2,4,26,32,33,39–41,51,76,87^
- multi-component foods/meals (e.g., instant mashed potatoes),^36,43,44,46,60,63,64,74^
- grains (e.g., microwave popcorn),^43,44,46^
- snacks,^63^
- sweets (e.g., cookie dough, RTB desserts),^33,39,43,46,63^
- and vegetables (e.g., pre-cut fresh vegetables).^26^

Figure 5-g shows the breakdown of RTC/RTB food groups. The share for proteins increased for this category, mainly because bacon was included in the processed meat category of many articles. The shares for vegetables and snacks decreased, and the dairy, fruit, and other categories were not represented in the RTC/RTB level of convenience.

Figure 5-g Ready-to-Cook/Ready-to-Bake Food Groups

This figure shows the breakdown of RTC/RTB food groups. 11 articles examined RTC/RTB proteins, 8 examined RTC/RTB multi-component foods/meals, 5 examined RTC/RTB sweets, 3 examined RTC/RTB grains, and 1 each examined RTC/RTB snacks and vegetables.

##### Ready-to-prepare food groups

There were only 3 groups represented in the RTP category. From most to least common:

- sweets (e.g., baking mixes),^2,4,26,33,39,40,44,60^
- grains (e.g., pancake mix),^12,40,43^
- and multi-component foods/meals (e.g., boxed mac and cheese).^20^

Figure 5-h shows the breakdown of RTP food groups. The share for sweets dominated this category, the share for multi-component foods/meals decreased substantially, and RTP vegetables, snacks, and proteins were not found in the literature.

Figure 5-h Ready-to-Prepare Food Groups

This figure shows the breakdown of RTP food groups. 8 articles examined RTP sweets, 3 examined RTP grains, and 1 examined RTP multi-component foods/meals.

### Research recommendations

1. Establish and use standard definitions for at-home convenience foods, RTE, RTH, RTP, RTC, and RTB to improve their identification, as well as the ability to compare results between studies.
2. Provide sufficient detail about specific foods included in a food category to help determine whether the outcome fits the eligibility criteria of at-home convenience foods.

## References of the articles included in the convenience food evidence scan

1 Litton MM, Beavers AW. The relationship between food security status and fruit and vegetable intake during the covid-19 pandemic. Nutrients. 2021;13(3):1–14. doi: 10.3390/nu13030712.
2 Lacko A, Maselko J, Popkin B, Ng SW. Socioeconomic and racial/ethnic disparities in the nutritional quality of packaged food purchases in the U.S., 2008-2018. Public Health Nutrition. 2021. doi: 10.1017/S1368980021000367.
3 Winham DM, Davitt ED, Heer MM, Shelley MC. Pulse knowledge, attitudes, practices, and cooking experience of midwestern us university students. Nutrients. 2020;12(11):1–13. doi: 10.3390/nu12113499.
4 Lacko A, Ng SW, Popkin B. Urban vs.. Rural socioeconomic differences in the nutritional quality of household packaged food purchases by store type. International Journal of Environmental Research and Public Health. 2020;17(20):1–22. doi: 10.3390/ijerph17207637.
5 Tseng M, Mastrantonio C, Glanz H, Volpe RJ, Iii N, D. B N. Fruit and Vegetable Purchasing Patterns and Supplemental Nutrition Assistance Program Participation: Findings From a Nationally Representative Survey. Journal of the Academy of Nutrition and Dietetics. 2020;120(10):1633–1642. doi: 10.1016/j.jand.2020.05.016.32736954
6 Zhang Q, Zhang J, Park K, Tang C. Association between usage of an app to redeem prescribed food benefits and redemption behaviors among the special supplemental nutrition program for women, infants, and children participants: Cross-sectional study. JMIR mHealth and uHealth. 2020;8(10). doi: 10.2196/20720.
7 Kwon S, Wang-Schweig M, Kandula NR. Body composition, physical activity, and convenience food consumption among asian american youth: 2011–2018 NHANES. International Journal of Environmental Research and Public Health. 2020;17(17):1–13. doi: 10.3390/ijerph17176187.
8 Palmer SM, Winham DM. Midwest consumer shopping habits, nutrition knowledge, and latino tienda use. Health Behavior and Policy Review. 2020;7(2):79–91. doi: 10.14485/HBPR.7.2.1.
9 Lyonnais MJ, Rafferty AP, Pitts SJ, Blanchard RJ, Kaur AP. Examining shopping patterns, use of food-related resources, and proposed solutions to improve healthy food access among food insecure and food secure Eastern North Carolina residents. International Journal of Environmental Research and Public Health. 2020;17(10). doi: 10.3390/ijerph17103361.
10 Overcash F, Davey C, Zhang Y, Reicks M. Evening meal types and family meal characteristics: Associations with demographic characteristics and food intake among adolescents. Nutrients. 2020;12(4). doi: 10.3390/nu12040886.
11 Heer MM, Winham DM. Bean preferences vary by acculturation level among latinas and by ethnicity with non-hispanic white women. International Journal of Environmental Research and Public Health. 2020;17(6). doi: 10.3390/ijerph17062100.
12 Rex SM, Trabulsi J, Baker S, Bodt B, Robson SM. Food Purchasing Behaviors of WIC Participants: What Non-WIC Eligible Foods Items Are Being Purchased. American Journal of Health Promotion. 2020;34(3):307–310. doi: 10.1177/0890117119892765.31854196
13 Wolfson JA, Lahne J, Raj M, Insolera N, Lavelle F, Dean M. Food agency in the united states: Associations with cooking behavior and dietary intake. Nutrients. 2020;12(3). doi: 10.3390/nu12030877.
14 Heer MM, Winham DM. Food behaviors, health, and bean nutrition awareness among low-income men: A pilot study. International Journal of Environmental Research and Public Health. 2020;17(3). doi: 10.3390/ijerph17031039.
15 Palmer SM, Knoblauch ST, Winham DM, Hiller MB, Shelley MC. Putting knowledge into practice: Low-income women talk about food choice decisions. International Journal of Environmental Research and Public Health. 2020;17(14):1–16. doi: 10.3390/ijerph17145092.
16 Sullivan VK, Na M, Proctor DN, Kris-Etherton PM, Petersen KS. Consumption of Dried Fruits Is Associated with Greater Intakes of Underconsumed Nutrients, Higher Total Energy Intakes, and Better Diet Quality in US Adults: A Cross-Sectional Analysis of the National Health and Nutrition Examination Survey, 2007-2016. Journal of the Academy of Nutrition and Dietetics. 2020. doi: 10.1016/j.jand.2020.08.085.
17 Zhu Y, Jain N, Vanage V, Holschuh N, Agler AH, Smith JD. Association between ready-to-eat cereal consumption and nutrient intake, nutritional adequacy, and diet quality in adults in the national health and nutrition examination survey 2015-2016. Nutrients. 2019;11(12). doi: 10.3390/nu11122952.
18 Franckle RL, Thorndike AN, Moran AJ, . Supermarket Purchases Over the Supplemental Nutrition Assistance Program Benefit Month: A Comparison Between Participants and Nonparticipants. American Journal of Preventive Medicine. 2019;57(6):800–807. doi: 10.1016/j.amepre.2019.07.025.31753261
19 Smith JD, Zhu Y, Vanage V, Jain N, Holschuh N, Agler AH. Association between ready-to-eat cereal consumption and nutrient intake, nutritional adequacy, and diet quality among infants, toddlers, and children in the national health and nutrition examination survey 2015-2016. Nutrients. 2019;11(9). doi: 10.3390/nu11091989.
20 Fertig AR, Loth KA, Trofholz AC, . Compared to Pre-prepared Meals, Fully and Partly Home-Cooked Meals in Diverse Families with Young Children Are More Likely to Include Nutritious Ingredients. Journal of the Academy of Nutrition and Dietetics. 2019;119(5):818–830. doi: 10.1016/j.jand.2018.12.006.30765316
21 Fulgoni VL, Iii B, M F, L C. Oatmeal-containing breakfast is associated with better diet quality and higher intake of key food groups and nutrients compared to other breakfasts in children. Nutrients. 2019;11(5). doi: 10.3390/nu11050964.
22 Bowen ME, Casola AR, Coleman C, Monahan L. Community Food Pantry (CFP) Recipients’ Food Challenges: Latino Households with at Least One Member Working as Farm Worker Compared to Other CFP Households. Journal of Hunger and Environmental Nutrition. 2019;14(1–2):128–140.
23 French SA, Tangney CC, Crane MM, Wang Y, Appelhans BM. Nutrition quality of food purchases varies by household income: The SHoPPER study. BMC Public Health. 2019;19(1). doi: 10.1186/s12889-019-6546-2.
24 Winham DM, Tisue ME, Palmer SM, Cichy KA, Shelley MC. Dry bean preferences and attitudes among midwest hispanic and non-hispanic white women. Nutrients. 2019;11(1). doi: 10.3390/nu11010178.
25 Babatunde OT, Briley PM, White BM, Fang X, Ellis C. Dietary Practices Among Stroke-survivors—Racial/Ethnic Differences. Journal of Stroke and Cerebrovascular Diseases. 2018;27(11):2926–2931. doi: 10.1016/j.jstrokecerebrovasdis.2018.06.026.30122627
26 Taillie LS, Grummon AH, Miles DR. Nutritional Profile of Purchases by Store Type: Disparities by Income and Food Program Participation. American Journal of Preventive Medicine. 2018;55(2):167–177. doi: 10.1016/j.amepre.2018.04.024.29910116
27 Ng SW, Hollingsworth BA, Busey EA, Wandell JL, Miles DR, Poti JM. Federal Nutrition Program Revisions Impact Low-income Households’ Food Purchases. American Journal of Preventive Medicine. 2018;54(3):403–412. doi: 10.1016/j.amepre.2017.12.003.29455757
28 Storey M, Anderson P. Total fruit and vegetable consumption increases among consumers of frozen fruit and vegetables. Nutrition. 2018;46:115–121. doi: 10.1016/j.nut.2017.08.013.29290348
29 Kornrich S, Roberts A. Household Income, Women’s Earnings, and Spending on Household Services, 1980–2010. Journal of Marriage and Family. 2018;80(1):150–165. doi: 10.1111/jomf.12450.
30 Dominick SR, Bir C, Widmar NO, Acharya L, Holly Wang H, Wilcox M. Exploring preferences beyond the (cereal) box: Ready-to-eat breakfast cereal buying behaviors. International Food and Agribusiness Management Review. 2018;21(8):1185–1201. doi: 10.22434/IFAMR2017.0113.
31 Taillie LS, Ng SW, Xue Y, Harding M. Deal or no deal? The prevalence and nutritional quality of price promotions among U.S. food and beverage purchases. Appetite. 2017;117:365–372. doi: 10.1016/j.appet.2017.07.006.28705473
32 Franckle RL, Moran A, Hou T, . Transactions at a Northeastern Supermarket Chain: Differences by Supplemental Nutrition Assistance Program Use. American Journal of Preventive Medicine. 2017;53(4):e131–e138. doi: 10.1016/j.amepre.2017.06.019.28818413
33 Grummon AH, Taillie LS. Nutritional profile of Supplemental Nutrition Assistance Program household food and beverage purchases. American Journal of Clinical Nutrition. 2017;105(6):1433–1442. doi: 10.3945/ajcn.116.147173.28424188
34 Gustat J, Lee YS, O’Malley K, . Personal characteristics, cooking at home and shopping frequency influence consumption. Preventive Medicine Reports. 2017;6:104–110. doi: 10.1016/j.pmedr.2017.02.007.28280684
35 Surathkal P, Dey MM, Engle CR, Chidmi B, Singh K. Consumer demand for frozen seafood product categories in the United States. Aquaculture Economics and Management. 2017;21(1):9–24. doi: 10.1080/13657305.2017.1265020.
36 Horning ML, Fulkerson JA, Friend SE, Story M. Reasons Parents Buy Prepackaged, Processed Meals: It Is More Complicated Than “I Don’t Have Time”. Journal of Nutrition Education and Behavior. 2017;49(1):60–66.e61. doi: 10.1016/j.jneb.2016.08.012.27743860
37 Errisuriz VL, Pasch KE, Perry CL. Perceived stress and dietary choices: The moderating role of stress management. Eating Behaviors. 2016;22:211–216. doi: 10.1016/j.eatbeh.2016.06.008.27310611
38 Freedman MR, Fulgoni VL. Canned Vegetable and Fruit Consumption Is Associated with Changes in Nutrient Intake and Higher Diet Quality in Children and Adults: National Health and Nutrition Examination Survey 2001-2010. Journal of the Academy of Nutrition and Dietetics. 2016;116(6):940–948. doi: 10.1016/j.jand.2015.10.013.26617186
39 Stern D, Poti JM, Ng SW, Robinson WR, Gordon-Larsen P, Popkin BM. Where people shop is not associated with the nutrient quality of packaged foods for any racial-ethnic group in the United States. American Journal of Clinical Nutrition. 2016;103(4):1125–1134. doi: 10.3945/ajcn.115.121806.26912495
40 Taillie LS, Ng SW, Popkin BM. Walmart and Other Food Retail Chains: Trends and Disparities in the Nutritional Profile of Packaged Food Purchases. American Journal of Preventive Medicine. 2016;50(2):171–179. doi: 10.1016/j.amepre.2015.07.015.26497262
41 Stern D, Ng SW, Popkin BM. The Nutrient Content of U.S. Household Food Purchases by Store Type. American Journal of Preventive Medicine. 2016;50(2):180–190. doi: 10.1016/j.amepre.2015.07.025.26437868
42 Wolfson JA, Bleich SN, Smith KC, Frattaroli S. What does cooking mean to you?: Perceptions of cooking and factors related to cooking behavior. Appetite. 2016;97:146–154. doi: 10.1016/j.appet.2015.11.030.26654888
43 Poti JM, Mendez MA, Ng SW, Popkin BM. Highly processed and ready-to-eat packaged food and beverage purchases differ by race/ethnicity among US households. Journal of Nutrition. 2016;146(9):1722–1730. doi: 10.3945/jn.116.230441.27466605
44 Eicher-Miller HA, Fulgoni VL, Iii K. Processed food contributions to energy and nutrient intake differ among US children by race/ethnicity. Nutrients. 2015;7(12):10076–10088. doi: 10.3390/nu7125503.26633491
45 Comerford KB. Frequent canned food use is positively associated with nutrient-dense food group consumption and higher nutrient intakes in US children and adults. Nutrients. 2015;7(7):5586–5600. doi: 10.3390/nu7075240.26184294
46 Poti JM, Mendez MA, Ng SW, Popkin BM. Is the degree of food processing and convenience linked with the nutritional quality of foods purchased by US households? American Journal of Clinical Nutrition. 2015;101(6):1251–1262. doi: 10.3945/ajcn.114.100925.25948666
47 Langellier BA, Brookmeyer R, Wang MC, Glik D. Language use affects food behaviours and food values among Mexican-origin adults in the USA. Public Health Nutrition. 2015;18(2):264–274. doi: 10.1017/S1368980014000287.24698136
48 Leslie T, Pawloski L, Kallman-Price J, . Survey of health status, nutrition and geography of food selection of chronic liver disease patients. Annals of Hepatology. 2014;13(5):533–540. doi: 10.1016/s1665-2681(19)31253-0.25152986
49 Ford CN, Ng SW, Popkin BM. Are food and beverage purchases in households with preschoolers changing?: A longitudinal analysis from 2000 to 2011. American Journal of Preventive Medicine. 2014;47(3):275–282. doi: 10.1016/j.amepre.2014.05.007.25049217
50 Reicks M, Jonnalagadda S, Albertson AM, Joshi N. Total dietary fiber intakes in the US population are related to whole grain consumption: Results from the National Health and Nutrition Examination Survey 2009 to 2010. Nutrition Research. 2014;34(3):226–234. doi: 10.1016/j.nutres.2014.01.002.24655489
51 Slining MM, Mathias KC, Popkin BM. Trends in Food and Beverage Sources among US Children and Adolescents: 1989-2010. Journal of the Academy of Nutrition and Dietetics. 2013;113(12):1683–1694. doi: 10.1016/j.jand.2013.06.001.23916972
52 Nackers LM, Appelhans BM. Food insecurity is linked to a food environment promoting obesity in households with children. Journal of Nutrition Education and Behavior. 2013;45(6):780–784. doi: 10.1016/j.jneb.2013.08.001.24021456
53 Albertson AM, Franko DL, Thompson DR, Tuttle C, Holschuh NM. Ready-to-Eat Cereal Intake is Associated with an Improved Nutrient Intake Profile among Food Insecure Children in the United States. Journal of Hunger and Environmental Nutrition. 2013;8(2):200–220. doi: 10.1080/19320248.2013.786664.
54 Ma Y, Ailawadi KL, Grewal D. Soda versus cereal and sugar versus fat: Drivers of healthful food intake and the impact of diabetes diagnosis. Journal of Marketing. 2013;77(3):101–120. doi: 10.1509/jm.11.0443.
55 Albertson AM, Wold AC, Joshi N. Ready-to-eat cereal consumption patterns: The relationship to nutrient intake, whole grain intake, and body mass index in an older American population. Journal of Aging Research. 2012;2012. doi: 10.1155/2012/631310.
56 Castetbon K, Harris JL, Schwartz MB. Purchases of ready-to-eat cereals vary across US household sociodemographic categories according to nutritional value and advertising targets. Public Health Nutrition. 2012;15(8):1456–1465.22152703
57 Hearst MO, Pasch KE, Laska MN. Urban v. suburban perceptions of the neighbourhood food environment as correlates of adolescent food purchasing. Public Health Nutrition. 2012;15(2):299–306. doi: 10.1017/S1368980011002114.21859510
58 Cunningham TJ, Barradas DT, Rosenberg KD, May AL, Kroelinger CD, Ahluwalia IB. Is maternal food security a predictor of food and drink intake among toddlers in Oregon? Maternal and child health journal. 2012;16 Suppl 2:339–346. doi: 10.1007/s10995-012-1094-8.22907271
59 Kuchler F. Is it food quality or quantity that responds to changing income? Applied Economic Perspectives and Policy. 2011;33(2):205–221. doi: 10.1093/aepp/ppr002.
60 Lacko A, Delamater P, Gordon-Larsen P, Wen Ng S. Geographic patterns and socioeconomic differences in the nutritional quality of household packaged food purchases in the United States. Health Place. 2021;69:102567. doi: 10.1016/j.healthplace.2021.102567.33930729
61 Larson N, Laska MN, Neumark-Sztainer D. Food Insecurity, Diet Quality, Home Food Availability, and Health Risk Behaviors Among Emerging Adults: Findings From the EAT 2010–2018 Study. American Journal of Public Health. 2020;110(9):1422–1428. doi: 10.2105/AJPH.2020.305783.32673120
62 Rahko vs.ky I, Jo Y. Higher Incomes and Greater Time Constraints Lead to Purchasing More Convenience Foods. 2018;June 2018(05).
63 Okrent AM, Kumcu A. U.S. Households’ Demand for Convenience Foods. 2016:40.
64 Okrent A. Purchases of Foods by Convenience Type Driven by Prices, Income, and Advertising. 2016(10):1.
65 Rahko vs.ky I, Jo Y, Carlson A. Consumers Balance Time and Money in Purchasing Convenience Foods. 2018.
66 Hammons A, Olvera N, Teran-Garcia M, Villegas E, Fiese B. Mealtime resistance: Hispanic mothers’ perspectives on making healthy eating changes within the family. Appetite. 2021;159. doi: 10.1016/j.appet.2020.105046.
67 Trofholz A, Richardson K, Mohamed N, Vang C, Berge JM. How a Racially/Ethnically Diverse and Immigrant Sample Qualitatively Describes the Role of Traditional and Non-traditional Foods in Feeding Their Children. Journal of Immigrant and Minority Health. 2020;22(6):1155–1162. doi: 10.1007/s10903-020-00999-3.32219660
68 Askelson NM, Meier C, Baquero B, Friberg J, Montgomery D, Hradek C. Understanding the Process of Prioritizing Fruit and Vegetable Purchases in Families With Low Incomes: “A Peach May Not Fill You Up as Much as Hamburger”. Health Education and Behavior. 2018;45(5):817–823. doi: 10.1177/1090198117752790.29353547
69 Palmer SM, Winham DM, Oberhauser AM, Litchfield RE. Socio-ecological barriers to dry grain pulse consumption among low-income women: A mixed methods approach. Nutrients. 2018;10(8). doi: 10.3390/nu10081108.
70 Ugalde M, Brand L, Beltran A, . Mommio’s recipe box: Assessment of the cooking habits of mothers of preschoolers and their perceptions of recipes for a video game. JMIR Serious Games. 2017;5(4). doi: 10.2196/games.8142.
71 Tobey LN, Koenig HF, Brown NA, Manore MM. Reaching low-income mothers to improve family fruit and vegetable intake: Food hero social marketing campaign—research steps, development and testing. Nutrients. 2016;8(9). doi: 10.3390/nu8090562.
72 Griffith DM, Wooley AM, Allen JO. “I’m Ready to Eat and Grab Whatever I Can Get”: Determinants and Patterns of African American Men’s Eating Practices. Health Promotion Practice. 2013;14(2):181–188. doi: 10.1177/1524839912437789.22773618
73 DiSantis KI, Grier SA, Odoms-Young A, . What “price” means when buying food: Insights from a multisite qualitative study with Black Americans. American Journal of Public Health. 2013;103(3):516–522. doi: 10.2105/AJPH.2012.301149.23327261
74 Berge JM, Fertig AR, Trofholz A, Neumark-Sztainer D, Rogers E, Loth K. Associations between parental stress, parent feeding practices, and child eating behaviors within the context of food insecurity. Preventive Medicine Reports. 2020;19. doi: 10.1016/j.pmedr.2020.101146.
75 Winkler MR, Lenk KM, Erickson DJ, Caspi CE, Laska MN. Longitudinal fruit and vegetable sales in small food retailers: Response to a novel local food policy and variation by neighborhood socioeconomic status. International Journal of Environmental Research and Public Health. 2020;17(15):1–15. doi: 10.3390/ijerph17155480.
76 Chen D, Jaenicke EC, Volpe RJ. The Healthfulness of Food-at-Home Expenditures, the Local Food Environment, and Childhood Obesity. American Journal of Health Promotion. 2019;33(3):412–419. doi: 10.1177/0890117118786871.30004249
77 Rahko vs.ky I, Lin BH, Lin CTJ, Lee JY. Effects of the Guiding Stars Program on purchases of ready-to-eat cereals with different nutritional attributes. Food Policy. 2013;43:100–107. doi: 10.1016/j.foodpol.2013.08.013.
78 Weatherspoon DD, Oehmke JF, Coleman MA, Dembele AS, Weatherspoon LJ. Will Long Term Food Desert Consumers Purchase Fresh Fruits and Vegetables? 2012;27(3):5.
79 Cassinat RA, Bruening M, Crespo NC, . Effects of a community-based pilot intervention on home food availability among U.S. households. International Journal of Environmental Research and Public Health. 2020;17(22):1–11. doi: 10.3390/ijerph17228327.
80 Pharis ML, Colby L, Wagner A, Mallya G. Sales of healthy snacks and beverages following the implementation of healthy vending standards in City of Philadelphia vending machines. Public Health Nutrition. 2018;21(2):339–345. doi: 10.1017/S1368980017001914.29061207
81 Andreyeva T, Luedicke J. Incentivizing fruit and vegetable purchases among participants in the Special Supplemental Nutrition Program for Women, Infants, and Children. Public Health Nutrition. 2015;18(1):33–41. doi: 10.1017/S1368980014000512.24809502
82 Dannefer R, Williams DA, Baronberg S, Silver L. Healthy bodegas: Increasing and promoting healthy foods at corner stores in New York City. American Journal of Public Health. 2012;102(10):e27–e31. doi: 10.2105/AJPH.2011.300615.
83 Sutherland LA, Kaley LA, Fischer L. Guiding Stars: The effect of a nutrition navigation program on consumer purchases at the supermarket. American Journal of Clinical Nutrition. 2010;91(4):1090S–1094S. doi: 10.3945/ajcn.2010.28450C.20147468
84 Çakır M, Balagtas JV, Okrent AM, Urbina-Ramirez M. Effects of Package Size on Household Food Purchases. Applied Economic Perspectives and Policy. 2021;43(2):781–801. doi: 10.1093/aepp/ppz019.
85 Whiteside-Mansell L, Swindle TM. Evaluation of together we inspire smart eating: Pre-school fruit and vegetable consumption. Health Education Research. 2019;34(1):72–83. doi: 10.1093/her/cyy048.30476080
86 Rogus S, Athens J, Cantor J, Elbel B. Measuring Micro-Level Effects of a New Supermarket: Do Residents Within 0.5 Mile Have Improved Dietary Behaviors? Journal of the Academy of Nutrition and Dietetics. 2018;118(6):1037–1046. doi: 10.1016/j.jand.2017.06.360.28797794
87 Moran A, Thorndike A, Franckle R, . Financial incentives increase purchases of fruit and vegetables among lower-income households with children. Health Affairs. 2019;38(9):1557–1566. doi: 10.1377/hlthaff.2018.05420.31479362
88 Polacsek M, Moran A, Thorndike AN, . A Supermarket Double-Dollar Incentive Program Increases Purchases of Fresh Fruits and Vegetables Among Low-Income Families With Children: The Healthy Double Study. Journal of Nutrition Education and Behavior. 2018;50(3):217–228.e211. doi: 10.1016/j.jneb.2017.09.013.29126661
89 Foster GD, Karpyn A, Wojtanowski AC, . Placement and promotion strategies to increase sales of healthier products in supermarkets in low-income, ethnically diverse neighborhoods: A randomized controlled trial. American Journal of Clinical Nutrition. 2014;99(6):1359–1368. doi: 10.3945/ajcn.113.075572.24695894