# Chapter 4 What is the relationship between income and time spent on food-at-home-related activities?

## Specific methods to conduct this rapid review

### Develop a protocol

The research question, “What is the relationship between income and time spent on food-at-home-related activities?” was answered using a rapid review.

The analytic framework for the rapid review examining the relationship between income and time spent on food-at-home-related activities is presented in Figure 4-a. This analytic framework visually represents the overall scope of the rapid review question, and depicts the contributing elements that were examined and evaluated. The intervention or exposure of interest is income (e.g., household, city, regional income) and income proxy (i.e., socioeconomic factor; geographic area; income-based federal assistance program participation/eligibility) in U.S. households or populations. The comparators are different levels/categories of income or income proxy. The outcome is time spent on food-at-home-related activities, including preparation, cooking, and cleaning in U.S. households or populations. The key confounders are food-away-from-home and household characteristics (e.g., household size (e.g., number of children, number of adults), single or dual head of household; marital status; level of employment; workload division). NESR analysts made a post-hoc change when assessing the risk of bias for confounding. NESR analysts determined that adjusting for food-away-from-home would be over controlling for the outcome due to the collinearity of time spent on food-at-home-related activities and time spent on food-away-from-home activities. Therefore, articles that did not account for food-away-from-home in their analyses were not rated differently for risk of bias due to confounding. The other factors to be considered are food security; race/ethnicity; sex; seasonal differences; urban/rural; cultural food choices; neighborhood characteristics (e.g., access to food/distance to stores/access to car/type of store); use of convenience foods; time preferences/value of food-related activities or cooking skills or cooking equipment. The confounders and other factors to be considered may impact the relationships of interest.

Figure 4-a Analytic framework for the rapid review on income and time spent on food-at-home-related activities

### Search for and select studies

The following outlines any departures from the search and select studies project methods for this specific rapid review:

- Articles were screened at the title, abstract, and the full-text level, separately.
- One person screened 100% of the articles and a 2^nd^ person screened 20% of articles at the title and abstract screening levels. All articles were dual-screened at the full-text level (2^nd^ person verified excluded articles). Included articles were hand-searched.

NESR analysts worked jointly with NEAT staff to establish the final inclusion and exclusion criteria and literature search strategy, which are detailed in Table 4-a and Appendix 4-a, respectively.

Table 4-a Inclusion and exclusion criteria for the rapid review on income and time spent on food-at-home-related activities

Category | Inclusion Criteria | Exclusion Criteria
Study design | - Any study design that is not a narrative review, systematic review, or meta-analysis | - Narrative reviews; - Systematic reviews; - Meta-analyses
Intervention/exposure | - Income (e.g., household, city, regional income); - Income proxy:; ○ Socioeconomic factor (e.g., education); ○ Geographic area; ○ Income-based Federal assistance program participation/eligibility | - Income proxies that are not a direct proxy for income determined by the author
Comparator | - Different levels or categories of income or SES factor proxy for income; - Higher vs. lower income geographic areas; - Different participation/eligibility status in income-based Federal assistance program(s) | - Comparison of geographic areas without a proxy for income
Outcomes | - Time spent on food-at-home-related activities:; ○ Preparation (e.g., cutting food, setting table, transportation, shopping); ○ Cooking; ○ Cleaning, including storing and putting away food/drinks; - Studies that examine transportation, shopping, and/or eating as part of a combined measure that also includes either preparation, cooking, and/or cleaning | - Studies that only examine time spent on transportation, shopping, and/or eating; - Studies that only examine time spent on snacking; - Time spent on food-away-from-home-related activities, including fast-food (FF) or full-service (FS) restaurants; Definitions (ERS, 2018):; - [underlined: Food-away-from-home:] Food prepared outside of home and includes food from FS restaurants and FF restaurants; - [underlined: Fast-food restaurants:] Eating places where consumers pay before they eat (e.g., bakery, burger restaurant, and sandwich or coffee shop); - [underlined: Full-service restaurants:] Eating places where consumers eat before they pay
Date of publication and data examined | - Published January 2008 – April 2021 and data inclusive of 2008 (e.g., 2000-2012; 2008-2009) | - Articles published prior to January 2008; - Data prior to 2008 (e.g., 2000-2007; 1999-2005)
Publication status | - Articles published in peer-review journals; - Grey literature: reports that have not been peer-reviewed but are available from government and non-governmental organizations | - Articles that have not been peer-reviewed and are not published in peer-reviewed journals, other than reports from government and non-governmental organizations
Language | - Articles published in English | - Articles published in languages other than English
Country | - Studies in the U.S. | - Studies conducted outside the U.S.
Study participants | - Human participants/populations | - Non-human participants (e.g., animal studies, in-vitro models)

### Extract data and assess the risk of bias

NESR analysts extracted and summarized data from each included article to objectively describe the body of evidence available to answer a rapid review question. The following outlines any departures from the extract data and assess risk of bias project methods for this specific rapid review:

- One NESR analyst extracted data (author, year, study design, cohort, year that time data were collected, data source for time, year that income data were collected, data source for income, analytic N, geographic location, location description, population description, intervention/exposure description, comparator, outcome type (preparation, cooking, and/or cleaning), outcome description, outcome definition, results, results summary, key confounders, other factors to be considered) and a 2^nd^ analyst verified the results.
- Risk of bias assessment was completed by 1 NESR analyst and verified by a 2^nd^ analyst.

### Synthesize the evidence

Evidence synthesis was completed by describing the evidence and evaluating the included studies individually and collectively as previously described in the project methods.

### Summary statements

NESR analysts formed summary statements, as previously described in the project methods, outlining the themes observed during the data synthesis of studies examining income and time spent on food-at-home-related activities.

### Recommend future research

Recommendations for future research evaluating the relationship between income and time spent on food-at-home-related activities were determined based on the gaps and limitations observed during data extraction and synthesis, as previously described in the project methods. Future work addressing these gaps and limitations may contribute to the body of evidence available to answer this research question.

## Results

### Literature search and screening results

The literature search yielded 5,499 search results after the removal of duplicates (see Figure 4-b). Dual screening resulted in the exclusion of 5,271 titles, 136 abstracts, and 79 full-texts articles. Reasons for full-text exclusion are in Appendix 4-b. One additional article was identified from the manual search. The body of evidence included 13 articles.

Figure 4-b Literature search and screen flowchart for the rapid review on income and time spent on food-at-home-related activities

### Description of the evidence

Thirteen studies (13 articles) were included in the body of evidence that addressed the relationship between income, including income proxy, and time spent on food-at-home-related activities (see Figure 4-b). Basic characteristics and results are shown in Table 4-b. All studies were cross-sectional. The majority (85%) of studies included populations that were nationally representative.^1–11^ One study each was conducted in Seattle, Washington,^12^ and Minneapolis and St. Paul, Minnesota.^13^ Studies generally included men and women with and without children. Of the five studies that reported race/ethnicity,^3,6,7,12,13^ all but one^13^ had predominantly (>65%) non-Hispanic White populations. The study conducted in Minneapolis and St. Paul, Minnesota had 28% White, 23% African American, 21% Asian, 17% Hispanic, and 11% mixed or other race/ethnicity participants.^13^ Therefore, the study populations for the majority of studies represent the racial/ethnic diversity of the U.S. population. The sample sizes in these 13 studies were large, ranging from 1,078^1^ to 118,635.^10^

#### Study characteristics

The majority of studies included participants who completed the survey of interest and were adults 18 years and older, regardless of marital status. Some exceptions were 1 study that only included adults aged 45-75 without children,^1^ another study that excluded participants with a child aged 16 to 17,^8^ and another study that only included Hispanic women with a child less than age 13.^9^ The years in which data were collected for analyses varied widely ranging from 2001-2018, and included 2006-2008^3,4,8^ and 2003-2011.^9,10^ Mean age of participants ranged from 32.8^9^ to 64.3 years.^1^

#### Exposure

Eight^1–4,8,10–12^ of the 13 included articles examined the effect of income on time spent on food-at-home-related activities. Gough et al.,^3^ Hamrick et al.,^4^ and Senia et al.,^8^ assessed time data from the American Time Use Survey (ATUS) from 2006-2008, and therefore, likely include some of the same data in their analyses. However, data eligibility criteria differed between these studies and all were included, given that their samples may not be entirely overlapping. Gough et al.,^3^ only included women and also included participants who completed 2014-2015 ATUS, Hamrick et al.,^4^ included anyone who completed the 8^th^ Current Population Survey, and Senia et al.,^8^ included anyone who are the only adult members (≥18 years) in the household and with no children age 16-17.

One study examined both income above or below the poverty threshold and SNAP participation and eligibility. Of the studies that examined income, 1 study examined labor income (income from wages, salary, tips, commissions, bonuses, and military pay) and non-labor income (income from government transfers (e.g., social security, disability, welfare), pension benefits, and any income from assets) separately.^1^ The federal poverty threshold, 130%, and 185% were used as cut-off points in numerous articles, possibly with overlapping data.^3,4,8^ For example, a study compared moderate/upper income, defined as ≥185% the poverty threshold to low income (130 to <185% poverty threshold) and to sub-poverty (<130% poverty threshold).^3^ Two studies had different income cut-offs of <$50,000 versus $50,000-99,999 versus ≥$100,000^12^ and <$25,000 versus $25,000-59,000 versus ≥$60,000.^11^ Three^2,3,10^ of these studies collected income data from the American Time Use Survey during various years from 2003-2012 and two from the Eating and Health Module,^4,8^ a supplement of the ATUS. Studies also used income data from the Health and Retirement Survey,^1^ the Home Cooking Survey,^11^ and a study-specific survey.^12^

Six^4–7,9,13^ of the 13 included articles examined the effect of income proxies on time spent on food-at-home-related activities. Although there may be overlapping data between Raschke et al.,^6^ Hamrick et al.,^4^ and Sliwa et al.,^9^ all of these studies had different date ranges of 2003-2009, 2006-2008, and 2003-2011 and therefore, the samples may not be entirely overlapping. Three^4–6^ of these studies examined SNAP participation and/or eligibility, 1 study compared different levels of employment (i.e., not employed versus part-time versus full-time),^13^ 1 study compared those who worked from home (higher income) to those who worked away from home (lower income),^7^ and 1 study compared US-born Hispanic mothers (higher income) to immigrant or migrant Hispanic mothers (lower income).^9^ The data source and years for the income proxies varied from 2003-2018 and included the American Time Use Survey,^6,9^ Eating and Health Module,^4^ Consumer Expenditure Quarterly Interview Survey,^5^ Leave and Job Flexibilities Module,^7^ and a study-specific survey.^13^

#### Outcome

The studies differed in their definition of the outcome of time spent on food-at-home-related activities. Twelve^1–10,12,13^ of the 13 included articles had “preparation” as part of their definition for food-at-home-related activities. As part of the outcome definition, 9 studies^1,4,6–12^ included “cleaning,” 6 studies^5,6,8,9,11,12^ included “cooking,” 5 studies^2,4,6,7,9^ included “presentation,” and 3 studies^5,7,8^ included both grocery shopping and transportation. Nine of the articles assessed time spent on food-at-home-related activities using the American Time Use Survey^2,3,5–10^ and/or the Eating and Health Module,^4,8^ 2 studies used a study-specific survey,^12,13^ and 1 study each used the Consumption and Activities Mail Survey^1^ and the Home Cooking Survey.^11^

### Synthesis of the evidence

#### Income

Among the 4 studies from 5 articles^2,4,8,11,12^ that included men and women, there were mixed findings. Three studies^2,8,11^ found no association between income (log family income or $25,000-59,999 versus ≥$60,000) and time spent on preparing and/or cooking, cleaning, food-related travel and grocery shopping. One of these studies did not describe how income was assessed and did not report model adjustments.^2^ Two studies found a significant and positive relationship between income and time spent on cooking and cleaning^11^ and preparing, cooking, and cleaning.^12^ It is important to note that the income comparators (<$25,000 to $25,000-59,000 and to ≥$60,000^11^ and <$50,000 to ≥$50,000^12^) were higher than the exposure and comparators in studies that found an inverse relationship between income and time spent on food-at-home-related activities. The 2 studies that found a significant and inverse relationship (i.e., higher income associated with less time spent on food-at-home-related activities) compared below or above 185% poverty threshold^4^ and below 130% poverty threshold to 130-185% poverty threshold.^8^

Three studies^1,3,10^ assessed the relationship between income among women only and time spent on food-at-home-related activities. There were mixed findings within these 3 studies. All 3 studies^1,3,10^ found a significant, inverse relationship between income in mothers and child-free women and time spent on food preparation and clean-up afterwards. Additionally, those with lower income levels tended to spend more time on food preparation. In 1 study, mothers with sub-poverty income (<130% poverty threshold) spent an average of 8.16 more minutes and mothers with low income (130% to <185% poverty threshold) spent 3.28 more minutes in food preparation per day than mothers with middle/upper income (≥185% poverty threshold).^3^ This was no longer significant among childfree women.^3^ Another study^1^ found an inverse relationship but this was between non-labor income, defined as income from government transfers (e.g., social security, disability, welfare), pension benefits, and any income from assets. No studies found a direct relationship. Overall, women, especially those with children, spend less time on food-at-home-related activities as income increases.

Two studies^1,10^ assessed the relationship between income among men only and time spent on food-at-home-related activities. One study found an inverse relationship and 1 study found no relationship. Due to a limited number of studies and mixed findings, it is unclear whether there is a relationship between income and time spent on food-at-home-related activities for men.

#### Income proxies

Five studies from 6 articles^4–7,9,13^ examined income proxies, 2 (from 3 articles) of which examined SNAP participation and/or eligibility,^4–6^ 1 examined employment level (not employed versus part-time versus full-time),^13^ 1 examined immigrant or migrant Hispanic mothers compared to U.S.-born Hispanic mothers,^9^ and working away from home compared to working at home (higher income).^6^

##### SNAP participation/eligibility

All 2 studies from 3 articles^4–6^ that examined SNAP participation and/or eligibility found that those who participated in SNAP spent more time on food preparation, presentation, clean-up, cooking, food-related travel and/or grocery shopping than SNAP non-participants,^6^ and SNAP-eligible non-participants,^5^ and SNAP non-eligible^4^ non-participants. One of two studies that compared SNAP participation to SNAP eligible non-participants did not find a significant difference in time spent on food preparation, including travel time related to food preparation, cooking time, and grocery shopping time.^4^ Specifically, SNAP participants spent 74.7 minutes per day on meal preparation, compared to 72.8 minutes per day among SNAP-eligible non-participants, and 57.6 minutes per day among non-SNAP, non-eligible (income above the 130% poverty threshold) participants (N=37,832, p<0.10).^4^ Therefore, individuals who were ineligible for SNAP due to income spent significantly less time on meal preparation than SNAP participants or SNAP-eligible non-participants.^4^ Although there is a small body of evidence, there is consistent evidence that SNAP participants spent significantly more time on food-at-home-related activities than SNAP non-participants. It is less clear whether there is a difference between SNAP participants and SNAP-eligible non-participants on time spent on meal preparation and/or cooking, cleaning, presentation, grocery shopping, and food-related travel.

##### Other income proxies

Two of three studies that examined income proxies found a significant association with participants with lower income based on income proxies spending more time on food preparation only,^13^ food preparation, cooking, serving, and clean-up.^9^ U.S.-born Hispanic mothers (higher income, n=1,345) spent significantly less time (70.8 min/day) on food preparation, cooking, presentation, and clean-up than immigrant or migrant Hispanic mothers (lower income, n=2,277) of 107.8 minutes per day.^9^ There was a dose-response relationship between mother’s employment level (unemployed versus part-time versus full-time) and time spent on food preparation, with time spent on food preparation decreasing as level of employment increases.^13^ For men, those who worked full-time spent less time than those who worked part-time or who were unemployed. However, there was no significant difference between men who were unemployed and men who worked part-time and time spent on food preparation per week.^13^

One study found a significant, positive relationship, with those who worked away from home (higher income) spending more time on food preparation, presentation, clean-up, grocery shopping, and travel to grocery store (mean: 40.7 min/day, SE: 5.4) than those who worked at home (lower income; Mean: 30.3 min/day, SE: 1.2).^7^

#### Summary

The results of all 13 articles suggest that at lower income levels (i.e., 185%, 130% or poverty threshold cut-offs), particularly women, spent more time on food-at-home-related activities. When comparing income levels higher than 185% poverty threshold (i.e., <$50,000 versus ≥$50,000; <25,000 versus $25,000-50,000 or ≥$60,000), there is a significant, positive association between income and time spent on preparation, cooking, and/or cleaning.^11,12^ There is also a consistent pattern of SNAP participants spending significantly more time on food preparation, presentation, clean-up, grocery shopping, and/or food-related travel than SNAP non-participants, regardless of SNAP-eligibility.

##### Assessment of the evidence

Risk of bias: Half of the studies did not account for household characteristics, which included 1 of the following: household size, single or dual head of household, marital status, level of employment, or workload division (Table 4-d).

Consistency: There was some consistency of an inverse relationship between income and time spent on food-at-home-related activities, especially among women and when comparing at 130% and 185% poverty thresholds. Additionally, evidence was consistent with those who participated in SNAP spending significant more time on food-at-home-related activities than those who were SNAP non-participants, including those who were SNAP-eligible.

Directness: The majority of studies (62%) directly measured the income, comparator, outcomes, and population that are outlined in the Analytic Framework (Figure 4-a). The remaining studies measured income proxies, rather than income directly.

Precision: All studies had large sample sizes and relatively small measures of variance.

Generalizability: All studies were conducted in the U.S., with the majority (85%) of studies using nationally-represented data. Therefore, studies are representative of the U.S. population.

## Summary statements and research recommendations

### Summary statements

The findings of the rapid review are presented in the following summary statements.

##### Income

Evidence indicates that those with lower income spend more time on food-at-home-related activities, particularly among women in the U.S.

Among all women, participants with higher income (≥185% poverty threshold or above the poverty threshold) spend significantly less time on food preparation or food preparation and clean-up.

Among women without children, there was no association between income and time spent on food preparation or food preparation and clean-up.

Among men, there is not enough evidence to determine whether there is an association between income and time spent on food preparation and cleaning due to inconsistent findings.

##### Income proxies

SNAP participation/eligibility: A small but consistent body of evidence suggests that those who participate in SNAP, compared to those who do not participate in SNAP, spend significantly more time on food-at-home-related activities.

It is less clear whether there is a difference between SNAP participants and SNAP-eligible non-participants on meal preparation due to few studies and inconsistent findings.

Studies had serious risks of bias for confounding due to not adjusting for household characteristics. One study also had a serious risk of bias for deviations from intended exposures due to unbalanced co-exposures (i.e., education, race, marital status) between exposure and comparator groups.

Other income proxies: There is not enough evidence to determine whether there is a relationship between income proxies and time spent on food-at-home-related activities.

### Research recommendations

- Account for household characteristics (e.g., household size, single or dual head of household, marital status, level of employment, workload division) when examining the relationship between income and time spent on food-at-home-related activities.
- Increase use of consistent definition, assessment, and measurement of time spent on food-at-home-related activities.
- More research is needed to examine the effect of income on food-at-home-related activities, particularly in men.
- Determine eligibility in SNAP among SNAP non-participants when examining the effect of SNAP participation/eligibility on time spent on food-at-home-related activities.

Table 4-b Cross-sectional evidence examining the relationship between income and time spent on food-at-home-related activities^a^

Article | Population, N | Exposure and Comparator | Outcome Definition | Results | Model adjustments
Dunn, 2015 ^1^ | National; Working adults (45-75y) without children; N=1,078 | Labor income (wages, salary, tips, commissions, bonuses, military pay); continuous; Non-labor income (e.g., social security, disability, welfare, pension, income from assets); continuous; [underlined: Data source]: Health and Retirement Survey (2001-2009 odd years) | Time (min/week) spent on preparing meals and cleaning-up afterwards in previous week; [underlined: Data source]: Consumption and Activities Mail Survey (2001-2009 odd years) | Average marginal effects (SE) of time spent on meal preparation (minutes last week), Tobit model; [underlined: Single-headed households (per $10,000):]; Male labor income (n=171): −2.346 (4.475), p>0.05; Male non-labor income (n=171): 1.735 (4.364), p>0.05; Female labor income (n=481): −15.050 (4.748), p<0.01; Female non-labor income (n=481): 3.947 (3.013), p>0.05; [underlined: Dual-headed households (per $10,000):]; Male labor income (n=210): 0.450 (2.458), p>0.05; Male non-labor income (n=210): −0.684 (1.979), p>0.05; Female labor income (n=216): −12.759 (5.971), p<0.05; Female non-labor income (n=216): −0.441 (2.135), p>0.05 | Age, respondent, and year-fixed effects, labor supply, and household assets
Forrester, 2018 ^2^ | National; Households who completed their 8^th^ interview in the Current Population Survey; Mean age ranges from 35.24 (unmarried male) to 45.35 (two earner married male); N=37,713 | Income (not described); [underlined: Data source]: American Time Use Survey (ATUS; 2003-2012) | Food preparation and presentation; [underlined: Data source]: ATUS (2003-2012) | Mean time spent on food preparation and presentation does not show much variation within subcategories of income; Statistical test NR | NR
Gough, 2019 ^3^ | National; Women aged 18-55; 65% non-Hispanic White, 13% non-Hispanic Black, 15% Hispanic; Married 55%; Employment status: employed full time 54%, employed part time 19%, out of the labor force 21%, unemployed 6%; N=17,914 | Poverty Threshold (categorical):; - ≥ 185% poverty threshold; - 130 to <185% poverty threshold; - <130% poverty threshold; [underlined: Data source]: ATUS (2006-2008, 2014-2015) | Time spent in food preparation (yes/no and min/day among those who prepared food); [underlined: Data source]: ATUS (2006-2008, 2014-2015) | 65% of women spent any time preparing food (mean (SE): 54.38 (43.35) min/day, range: 1-210 min/day); [underlined: Mothers’ Likelihood of preparing food, n=8517]; OR (95% CI), logistic regression; Middle/Upper income: Ref; Low income (130-185% poverty threshold): 1.38 (1.15, 1.65), p<0.01; Sub-poverty income (<130% poverty threshold): 1.64 (1.39, 1.94), p<0.001; [underlined: Childfree Women’s Likelihood of preparing food, n=3198]; OR (95% CI), logistic regression; Middle/Upper income: Ref; Low income: 1.16 (0.89, 1.51), p>0.10; Sub-poverty income: 1.07 (0.86, 1.35), p>0.10; [underlined: Mothers’ average min/day in food preparation, n=8517]; Coefficient (SE), OLS regression; Middle/Upper income: Ref; Low income: 3.28 (1.91), p<0.10; Sub-poverty income: 8.16 (1.83), p<0.001; Low income vs. sub-poverty income, p is statistically significant; [underlined: Childfree Women’s average min/day in food preparation, n=3198]; Coefficient (SE), OLS regression (adjusted for age, marital status, education, race/ethnicity, citizenship, employment, urban residence, weekend day, and year); Middle/Upper income: Ref; Low income: 2.94 (3.21), p>0.10; Sub-poverty income: 4.91 (3.40), p>0.10 | Age, marital status, education, race/ethnicity, citizenship, employment, urban residence, weekend day, and year (all models)
Hamrick, 2011 ^4^ | National; Participants who completed the ATUS data and Eating and Health Module for 2006-2008; N=37,832 | Income (categorical):; - <185% poverty threshold; - >185% poverty threshold; - Income missing; [underlined: Data source]: Eating and Health Module (2006-2008) | Meal preparation defined as food and drink preparation, food presentation, kitchen and food cleanup; [underlined: Data source]: ATUS/Eating and Health Module (2006-2008) | [underlined: Mean meal prep time (minutes), total population, p<0.10]; Income <185% poverty threshold: 40.3; Income >185% poverty threshold: 29.5; Income missing: 40.2; [underlined: Mean meal prep time (minutes), participants, p<0.10]; Income <185% poverty threshold: 70.8; Income >185% poverty threshold: 56.4; Income missing: 75.3 | None
Monsivais, 2014 ^12^; Seattle Obesity Study | Seattle, WA; Participants who completed survey; mean age 54y, 67.4% women, 81% White, 7.5% African American, 6.7% Asian, 2.7% Hispanic, 2% other; N=1,319 | Household income (categorical):; - <$50,000/year; - $50,000-$99,999/year; - ≥$100,000/year; [underlined: Data source]: Study-specific survey (2008-2009) | Average hours spent on preparing, cooking, and cleaning up from meals each time.; Responses stratified into three groups:; <1 hr/day (n=212, 16%); 1-2 hrs/day (n=566, 43%); >2 hrs/day (n=541, 41%); [underlined: Data source]: Study-specific survey (2008-2009) | Household income >$50,000/year (%), Pearson chi-square; Hours/day spent preparing, cooking, and cleaning up from meals, p=0.005; <1 hr/day (n=212): 46.7%; 1-2 hrs/day (n=566): 58.3%; >2 hrs/day (n=541): 57.1% | None
Senia, 2017 ^8^ | National; Participants who completed ATUS/Eating and Health module, are the only adult member (≥18y) in a household with no children 16-17y; N=11,070 | Income (continuous); Income (categorical):; - 130-185% poverty; - <130% poverty; [underlined: Data source:] ATUS (2006-2008) | Preparing, cooking, cleaning time, food-related travel, grocery shopping; [underlined: Data source]: ATUS (2006-2008) | [underlined: Marginal effect (SE) of probability of positive food preparation duration]; Double-hurdle model:; <130% poverty: 0.04 (0.01), p<0.01; 130-185% poverty: 0.01 (0.01), p≥0.1; Log of real family income: −0.01 (0.00), p<0.01; [underlined: Marginal effect (SE) of expected duration of food preparation (min/day)]; Double-hurdle model; <130% poverty: 5.30 (1.35), p<0.01; 130-185% poverty: 3.72 (1.86), p<0.05; Log of real family income: −1.09 (0.68), p≥0.10 | Food-at-home and fast food price indices, age, sex, race/ethnicity, foreign-born, missing income, education, presence of child (0-5 and 6-15 y), metropolitan area, holiday, day of the week, region, year, season
Smith, 2014 ^10^ | National; Free-living residents of households in all 50 states and District of Columbia ≥18y; N=118,635 | Income (categorical):; - Below poverty (family income < weighted average poverty threshold for relevant year); - Above poverty threshold; [underlined: Data source]: ATUS (2003-2011) | Any time spent in food preparation or meal-related cleaning into 3 categorical variables by gender:; Female:; Not cooking: 32%; Cooking 1-59 min/day: 35%; Cooking ≥ 60 min/day: 33%; Male:; Not cooking: 60%; Cooking 1-39 min/day: 23%; Cooking ≥ 40 min/day: 17%; [underlined: Data source]: ATUS (2003-2011) | Men (n=51,139):; Percentage of men in each cooking category from 2003-2007 to 2008-2011 (post-recession), Multinomial logistic regression; [underlined: Below poverty:]; 0 minutes/day: 2003-2007: 62%, 2008-2011: 56%, Change: −6%; 1-39 minutes/day: 2003-2007: 22%, 2008-2011: 24%, Change: 2%; >=40 min/day: 2003-2007: 16%, 2008-2011: 20%, Change: 4%; [underlined: Above poverty:]; 0 minutes/day: 2003-2007: 61%, 2008-2011: 59%, Change: −2%; 1-39 minutes/day: 2003-2007: 22%, 2008-2011: 23%, Change: 1%; >=40 min/day: 2003-2007: 16%, 2008-2011: 18%, Change: 2%; Change in percentage of men cooking below (6%) vs. above (2%) poverty: p<0.01; Women (n=67,496): Household income below federal poverty threshold was associated with a strong and consistent increase in likelihood of women cooking for longer durations. | Holidays, age, education, race/ethnicity, household type, individual employment status, and state-level unemployment
Wolfson, 2019 ^11^ | National; Participants of the GfK KnowledgePanel (55,000 US adults recruited through equal probability, with sampling frame covering 97% of US households); N=1,112 | Income (categorical):; - Low income: < $25,000; - Middle income: $25,000–$59,000; - Highest income: ≥$60,000; [underlined: Data source]: Home Cooking Survey | Cooking and cleaning time defined as minutes that the participant, or someone in their household, typically spends cooking dinner and cleaning up after dinner on weekdays and on weekends.; [underlined: Data source]: Home Cooking Survey | Mean (SEM) time (min/day) spent on dinner cooking and cleaning, Multivariate negative binomial regression; [underlined: Weekday]; <$25,000: 44.87 (3.11); $25,000-59,000: 58.63 (2.27), vs. Low income, p<0.001; ≥$60,000: 53.11 (1.83), vs. Low income, p=0.03; [underlined: Weekend]; <$25,000: 44.55 (3.16); $25,000-59,000: 56.72 (2.39), vs. Low income, p=0.004; ≥$60,000: 53.53 (1.85), vs. Low income, p=0.02 | Income, gender, age, race/ethnicity, education, SNAP/WIC status, employment status, primary grocery shopper status

a Abbreviations: ATUS: American Time Use Survey; CI: confidence interval; min: minutes; NR: Not Reported; OLS: ordinary least-squares; OR: odds ratio; SE: standard error; SEM: standard error of mean; SNAP: Supplemental Nutrition Assistance Program; WIC: Special Supplemental Nutrition Program for Women, Infants and Children

Bold indicates statistically significant findings

Table 4-c Cross-sectional evidence examining the relationship between income proxy and time spent on food-at-home-related activities^a^

Article | Population, N | Exposure and Comparator(s) | Outcome Definition | Results | Model adjustments
Bauer, 2012 ^13^; Project F-EAT | Minneapolis and St. Paul, MN; Parents of adolescents who participated in the EAT 2010 study; age mean ranged from 40.6 to 45.4y; 71% in married/committed relationship; White n=961 (28%), African American/Black n=817 (23%), Hispanic n=592 (17%), Asian n=728 (21%), Mixed/other n=395 (11%); N=3,256 | [underlined: SES proxy]: Employment; - Not employed (lowest income); - Part time (middle income); - Full time (highest income); [underlined: Data source]: Study-specific survey (2009-2010) | Food preparation time (hours/week); [underlined: Data source]: Study-specific survey (2009-2010) | Adjusted means (SE) Time spent on food preparation (hours/week), Linear regression; [underlined: Fathers, p<0.001*]; Not employed (n=298): 7.4 (0.39) a; Part time (n=133): 6.8 (0.56) a; Full time (n=752): 4.7 (0.23) b (p<0.05); [underlined: Mothers, p<0.001]; Not employed (lowest income, n=760): 11.5 (0.30) a (p<0.05); Part time (middle income, n=368): 10.1 (0.41) b (p<0.05); Full time (highest income, n=945): 8.8 (0.26) c (p<0.05); *Different letters indicate statistically significant differences | Relationship status, race/ethnicity, education, age, language spoken at home, and number of children in home
Hamrick, 2011 ^4^ | National; Participants who completed the ATUS data and the Eating and Health Module for 2006-2008; N=37,832 | [underlined: SES proxy]: Participation and eligibility in SNAP/food stamps:; - SNAP participation; - Non-SNAP, income-eligible; - Non-SNAP, income >130% poverty threshold; [underlined: Data source]: Eating and Health Module (2006-2008) | Meal preparation defined as food and drink preparation, food presentation, kitchen and food cleanup; [underlined: Data source]: ATUS (2006-2008) | [underlined: Mean meal prep time (min/day), total population, p<0.10]; SNAP/FSP participation household: 47.9; Non-SNAP but income eligible: 39.9; Non-SNAP, income >130% poverty threshold: 30.4; [underlined: Mean meal prep time (min/day), participants, p<0.10]; SNAP/FSP participation household: 74.7; Non-SNAP but income eligible: 72.8; Non-SNAP, income >130% poverty threshold: 57.6 | None
Kim, 2020 ^5^ | National; Households with annual incomes <130% poverty threshold; N=8,408 | [underlined: SES proxy]:; - SNAP participant; - SNAP eligible non-participants; [underlined: Data source]: Consumer Expenditure Quarterly Interview Survey (2013-2014) | Time (min/day) spent in food preparation, including travel time related to food preparation, cooking time, and grocery shopping time; [underlined: Data source]: ATUS (2013-2014) | [underlined: Time (min/day) spent in food preparation, Regression difference-in-differences model Predicted mean (robust SE)]; Any SNAP: 8.065 (2.695), p<0.01; After: −0.104 (4.768), p>0.05; SNAP*After benefit decrease: −13.892 (4.127), p<0.01; R^2 = 0.159; [underlined: Time (min/day) spent cooking, Regression difference-in-differences model Predicted mean (robust SE)]; Any SNAP: 5.824 (2.156), p<0.01; R^2 = 0.162; Additionally adjusted for after SNAP benefit decrease | Education, age, age-squared, sex, race, labor force participation, family size, metropolitan, holiday indicator, and fixed effects for day, month, and state
Raschke, 2012 ^6^ | National; Participants aged 18-65y; N=18,740 | [underlined: SES proxy]: Hourly market wage by SNAP participation:; - SNAP participants (n=935): $10.90/hr; - SNAP non-participants (n=17,805): $21.01/hr; [underlined: Data source]: ATUS, Current Population Survey - Food Security Supplement (2003-2009) | Home food production (min/d), which includes food preparation, presentation, and clean up; [underlined: Data source]: ATUS (2003-2009) | Mean time (min/day) in home food production, Welch’s t-test, p<0.05; SNAP participants (lower income, n=935): 66.95; SNAP non-participants (higher income, n=17,805): 53.52 | None
Restrepo, 2020 ^7^ | National; Mean 39y, 54.4% female, 68.5% non-Hispanic White, 12.1% Hispanic, 9.7% non-Hispanic Black; N=1,784 | [underlined: SES proxy]:; - Worked away from home; - Worked from home; [underlined: Data source]: Leave and Job Flexibilities Module (2017-2018) | Food preparation includes food and drink preparation, food presentation, kitchen and food clean-up, grocery shopping, and travel to grocery store; [underlined: Data source]: ATUS (2017-2018) | Coefficient estimate (SE) food preparation in minutes/d, p<0.10; Worked away from home (lower income, n=1637): 30.3 (1.216); Worked from home (higher income, n=147): 40.7 (5.433) | None
Sliwa, 2015 ^9^ | National; Hispanic mothers with at least 1 child <13y; mean age 32.8y; 66.2% households with child under 6 (p<0.05 between exposure groups with more US-born mothers with children <6 than im/migrant mothers); 24% single mother household (p<0.05 between exposure groups with more US-born mothers having higher % of single mother household); N=3,622 | [underlined: SES proxy]:; - Im/migrant (n=2277): 52.8% <=130% of poverty guideline; 19.3% >130-185% of poverty guideline; 27.9% >185% of poverty guideline; - US-born (n=1345): 36.6% <=130% of poverty guideline; 16.6% >130-185% of poverty guideline; 46.7% >185% of poverty guideline; [underlined: Data source]: ATUS (2003-2011) | Food preparation defined as total minutes spent preparing, cooking, serving food, clean up (e.g., putting away food and drinks, tidying the kitchen); [underlined: Data source]: ATUS (2003-2011) | Mean (SE) daily food preparation (minutes), adjusted Wald test, p<0.001; Im/migrant (lower income, n=2277): 107.8 (2.0); US-born (higher income, n=1345): 70.8 (2.1) | Hours worked/8, worked late hours, Nativity X origin interaction, Education, Single mother, Number children in HH, presence of child <6, maternal age, weekend diary day, and survey year

a Abbreviations: ATUS: American Time Use Survey; min: minutes; FSP: Food Stamp Program; NR: Not Reported; OR: odds ratio; SE: standard error; SES: socioeconomic status; SNAP: Supplemental Nutrition Assistance Program; WIC: Special Supplemental Nutrition Program for Women, Infants and Children

Bold indicates statistically significant findings

Table 4-d Risk of bias for observational studies examining income and time spent on food-at-home-related activities^a^

Article | Confounding | Selection of participants | Classification of exposures | Deviations from intended exposures | Missing data | Outcome measurement | Selection of the reported result
Bauer, 2012^13^ | MODERATE | LOW | LOW | MODERATE | LOW | MODERATE | MODERATE
Dunn, 2015^1^ | MODERATE | MODERATE | LOW | LOW | MODERATE | MODERATE | MODERATE
Forrester, 2018^2^ | SERIOUS | LOW | SERIOUS | LOW | NO INFORMATION | MODERATE | MODERATE
Gough, 2019^3^ | MODERATE | LOW | LOW | LOW | MODERATE | MODERATE | MODERATE
Hamrick, 2011^4^ | SERIOUS | LOW | LOW | LOW | LOW | MODERATE | MODERATE
Kim, 2020^5^ | MODERATE | LOW | LOW | LOW | LOW | MODERATE | MODERATE
Monsivais, 2014^12^ | SERIOUS | LOW | LOW | LOW | MODERATE | MODERATE | MODERATE
Raschke, 2012^6^ | SERIOUS | LOW | LOW | SERIOUS | LOW | MODERATE | MODERATE
Restrepo, 2020^7^ | SERIOUS | MODERATE | MODERATE | SERIOUS | MODERATE | MODERATE | MODERATE
Senia, 2017^8^ | MODERATE | LOW | LOW | LOW | LOW | MODERATE | MODERATE
Sliwa, 2015^9^ | SERIOUS | LOW | MODERATE | SERIOUS | MODERATE | MODERATE | MODERATE
Smith, 2014^10^ | MODERATE | LOW | LOW | LOW | MODERATE | MODERATE | MODERATE
Wolfson, 2019^11^ | MODERATE | LOW | LOW | LOW | MODERATE | MODERATE | MODERATE

a Possible ratings of low, moderate, serious, critical, or no information determined using the “Risk of Bias for Nutrition Observational Studies” tool (RoB-NObs) ( Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC. )

## References of the articles included in the income and time spent on food-at-home-related activities rapid review

1 Bauer KW, Hearst MO, Escoto K, Berge JM, Neumark-Sztainer D. Parental employment and work-family stress: associations with family food environments. Soc Sci Med. 2012;75(3):496–504. doi:10.1016/j.socscimed.2012.03.026.22591825
2 Dunn RA. Labor supply and household meal production among working adults in the Health and Retirement Survey. Review of Economics of the Household. 2013;13(2):437–457. doi:10.1007/s11150-013-9223-8.
3 Forrester K, Klein J. An analysis of female labor supply, home production, and household consumption expenditures. J Demogr Econ. 2018;84(3):257–307. doi:10.1017/dem.2018.8.
4 Gough M, Lippert AM, Martin MA. The role of time use behaviors in the risk of obesity among low-income mothers. Women’s Health Issues. 2019;29(1):23–30. doi:10.1016/j.whi.2018.10.002.30446329
5 Hamrick KS, Andrews M, Guthrie J, Hopkins D, McClelland K. How much time do Americans spend on food? US Department of Agriculture, Economic Research Service. 2011;EIB-86.
6 Kim J, Rabbitt MP, Tuttle C. Changes in low-income households’ spending and time use patterns in response to the 2013 sunset of the ARRA-SNAP benefit. Applied Economic Perspectives and Policy. 2019;42(4):777–795. doi:10.1093/aepp/ppz007.
7 Monsivais P, Aggarwal A, Drewnowski A. Time spent on home food preparation and indicators of healthy eating. Am J Prev Med. 2014;47(6):796–802. doi:10.1016/j.amepre.2014.07.033.25245799
8 Raschke C. Food stamps and the time cost of food preparation. Review of Economics of the Household. 2011;10(2):259–275. doi:10.1007/s11150-011-9128-3.
9 Restrepo BJ, Zeballos E. The effect of working from home on major time allocations with a focus on food-related activities. Rev Econ Househ. 2020:1–23. doi:10.1007/s11150-020-09497-9.
10 Senia MC, Jensen HH, Zhylye vs.kyy O. Time in eating and food preparation among single adults. Review of Economics of the Household. 2014;15(2):399–432. doi:10.1007/s11150-014-9258-5.
11 Sliwa SA, Must A, Perea F, Economos CD. Maternal employment, acculturation, and time spent in food-related behaviors among Hispanic mothers in the United States. Evidence from the American Time Use Survey. Appetite. 2015;87:10–19. doi:10.1016/j.appet.2014.10.015.25451579
12 Smith LP, Ng SW, Popkin BM. Resistant to the recession: Low-income adults’ maintenance of cooking and away-from-home eating behaviors during times of economic turbulence. Am J Public Health. 2014;104(5):840–846. doi:10.2105/AJPH.2013.301677.24625145
13 Wolfson JA, Ramsing R, Richardson CR, Palmer A. Barriers to healthy food access: Associations with household income and cooking behavior. Prev Med Rep. 2019;13:298–305. doi:10.1016/j.pmedr.2019.01.023.30792944