# Chapter 3 What is the relationship between overall diet cost and following a dietary pattern that aligns with the Dietary Guidelines for Americans, as measured by the Healthy Eating Index (HEI)?

## Specific methods to conduct this rapid review

### Develop a protocol

The research question, “What is the relationship between overall diet cost and following a dietary pattern that aligns with the Dietary Guidelines for Americans, as measured by the Healthy Eating Index (HEI)?”, was answered using a rapid review.

The analytic framework for the rapid review examining the relationship between diet cost and HEI is presented in Figure 3-a. This analytic framework visually represents the overall scope of the rapid review question, and depicts the contributing elements that were examined and evaluated. The intervention or exposure of interest is overall diet cost in U.S. households or populations. The comparators are different levels or categories of overall diet cost, or the overall cost of a different diet(s). The outcomes are dietary patterns that align with the Dietary Guidelines for Americans, as measured by the HEI in U.S. households or populations. The key confounders are urban versus rural, cultural/racial diversity or disparities, sex, age, energy, and SES. The other factors to be considered are cultural food choices, neighborhood characteristics (e.g., access to food/distance to stores/access to car/type of store), smoking, weight status, chronic disease status, convenience level, processing level, and food security status. The confounders and other factors to be considered may impact the relationships of interest.

Figure 3-a Analytic framework

### Search for and select studies

The following outlines any departures from the search and select studies project methods for this specific rapid review:

- Title and abstract screening was completed together in 1 level and full text screening was at a separate level.
- For title and abstract screening, 80% of all records were single-screened and 20% of all records were dual-screened, independently. For the full-text screening level all records were dual-screened, independently by 2 analysts.

NESR analysts worked jointly with NEAT staff to establish the final inclusion and exclusion criteria and literature search strategy, which are detailed in Table 3-a and Appendix 3-a, respectively.

Table 3-a Inclusion and exclusion criteria

Category | Inclusion Criteria | Exclusion Criteria
Study design | - Any study design that is not a narrative review, systematic review, or meta-analysis | - Narrative reviews; - Systematic reviews; - Meta-analyses
Intervention/exposure | - Overall diet cost or change in overall diet cost; - Overall food expenditures or change in overall food expenditures; - All assessment methods of diet cost or expenditures will be included; - Measures that include labor or time within an overall diet cost or expenditure | - Individual food, beverage, food group, or multiple food group costs; - Costs of labor or time alone, that are not part of an overall diet cost measure
Comparator | - Different levels/categories of overall diet cost; - Overall cost of a different diet | - N/A
Outcomes | - Dietary patterns that specifically align with the Dietary Guidelines for Americans, as measured by the total Healthy Eating Index (HEI); - All versions or variations of HEI (e.g. HEI-2005, HEI-2010, HEI-2015); - Change in total HEI over time | - Studies that examine any other dietary pattern or diet quality indicator that include only individual or select foods and beverages and do not reflect the totality of the diet nor the Dietary Guidelines for Americans.; - Studies that only examine component scores of the HEI
Publication date | - Jan 2008 - May 2021 and data inclusive of 2008 (e.g., 2000-2012; 2008-2009) | - Articles published prior to Jan 2008; - Data prior to 2008 (e.g., 2000-2007; 1999-2005)
Publication status | - Articles published in peer-reviewed journals; - Grey literature: reports that have not been peer reviewed but are available from government and nongovernmental organizations | - Articles that have not been peer-reviewed and are not published in peer-reviewed journals, other than reports from government and nongovernmental organizations
Language | - Articles published in English | - Articles published in languages other than English
Country | - Studies conducted the U.S. | - Studies conducted in countries outside the U.S.
Study participants | - Human participants/populations; ○ Males; ○ Females | - Non-human participants (e.g., animal studies, in-vitro models)

### Extract data and assess the risk of bias

NESR analysts extracted and summarized data from each included article to objectively describe the body of evidence available to answer a rapid review question. The following outlines any departures from the extract data and assess risk of bias project methods for this specific rapid review:

- Data extraction and risk of bias assessment was completed on all included articles and verified by a 2^nd^ analyst.

### Synthesize the evidence

Evidence synthesis was completed by describing the evidence and evaluating the included studies individually and collectively as previously described in the project methods.

### Summary statements

NESR analysts formed summary statements, as previously described in the project methods, outlining the themes observed during the data synthesis of studies examining diet cost and HEI.

### Recommend future research

Recommendations for future research evaluating the relationship between diet cost and HEI were determined based on the gaps and limitations observed during data extraction and synthesis, as previously described in the project methods. Future work addressing these gaps and limitations may contribute to the body of evidence available to answer this research question.

## Results

### Literature search and screening results

The literature search yielded 3,335 search results after the removal of duplicates (see Figure 3-b). Screening resulted in the exclusion of 3,182 titles and abstracts, and 140 full-texts articles. Reasons for full-text exclusion are in Appendix 3-b. One additional article was identified for inclusion from the manual search. The body of evidence included 12 articles.

Figure 3-b Literature search and screen flowchart

### Description of evidence

This rapid review included 12 articles that examined the relationship between diet cost and HEI.^1–12^ One article was an RCT^9^, 2 were prospective cohort studies^3,12^, and the remaining 9 were cross-sectional studies.^1,2,4–8,10,11^ The sample sizes of the studies ranged from 134^9^ to 11,181^10^ participants or dyads. One sample size was unreported but used data from NHANES.^1^

#### Population characteristics

Seven independent study populations were examined in the 12 articles. Two articles used nationally representative data (NHANES),^1,10^ 3 articles were from the population included in the Seattle Obesity Study III (SOS III) study,^6,7,11^ 2 articles were from populations from the Healthy Aging in Neighborhoods of Diversity across the Life Span (HANDLS) study,^2,3^ and 2 articles came from the same population from Massachusetts.^8,9^ The remaining 3 articles were individual populations from Texas and Pennsylvania.^4,5,12^ Ten articles assessed only adults,^1–7,10–12^ 1 article assessed only children,^8^ and 1 article assessed child-parent dyads.^9^ While similar data were analyzed in the articles from the same study populations, each article contributed unique sub-analyses or analytic/assessment methods.

#### Exposure and comparator characteristics: diet cost and food expenditures

There were 2 categories of the exposure examined in the included articles, diet cost and food expenditures.

Eight articles assessed diet cost^6–11^ or monetary value of the diet^2,3^ that was based on the cost of the diet that was consumed by the participant. In this subset of studies, diet cost was estimated from consumption data, which were linked to external food prices, and used to calculate a diet cost. While this method most directly answers the question, it has the limitation that costs were estimated using databases that may not be reflective of what the participants paid for the food, the geographic locations that they lived or from the same period of time that the diet data was collected. The food price databases that were used varied across the studies, and included the CNPP Food Prices Database,^2,10^ UNC’s Packaged Food Purchase and Price Database,^3^ local retail prices from a large supermarket (i.e., Safeway),^6,7,11^ or national online supermarket prices.^8,9^ Diet costs were estimated either per day^2,3,8,9^ or per month.^6,7,10,11^

Seven articles assessed food expenditures^4–7,11,12^ or grocery spending^1^ that were based on the amount spent on purchases of food at home and/or food away from home. Two articles reported only expenditures from food at home,^7,11^ while the other 5 articles reported total food expenditures which included both food at home and food away from home.^4–6,12^ Expenditures were estimated from purchase data, either grocery receipts^12^ or a self-reported estimate of how much money they spent on food per capita^1,5–7,11,12^ or per household.^4^ One article did not report the method used for collecting expenditure data.^1^ Expenditures were generally adjusted to be reflective of the amount of time and number of people the expenditures represent. Two articles reported expenditures per week,^4,5^ while 4 articles reported expenditures per month.^6,7,11,12^ However, what is purchased by the study participant may not reflect what was actually consumed, and therefore, this approach is an indirect measure of the relationship being examined.

#### Outcome assessment: HEI score

All studies examined dietary patterns aligned with the DGA as measured by the HEI. Four articles assessed HEI-2015,^4,6,7,11^ 4 articles assessed HEI-2010,^2,3,10,12^ 3 articles assessed HEI-2005,^5,8,9^ and 1 article did not report which version of HEI was used in the analysis.^1^ Scores on the HEI were determined using a variety of validated dietary assessment methods, including food frequency questionnaires, 24-hour dietary recalls, or 3 day diet records.

### Synthesis

#### Diet cost

Eight articles assessed the cost of the diet and HEI by measuring diet cost as the exposure and results from these studies are provided in Table 3-b.^2,3,6–11^ Six^2,3,6,7,10,11^ of these 8 articles reported that higher cost diets had higher HEI scores or that lower cost diets had lower HEI scores. Three of the 6 articles with significant findings were from the SOS III cohort and included unique data that answered this question but were from the same population of participants.^6,7,11^

The 2 other articles (using data from 1 RCT) showed non-significant associations between diet cost and HEI scores.^8,9^ One article showed a non-significant time-varying association between higher diet costs and lower HEI scores over the 18 month intervention in both children and their parents. The other article, which was a cross sectional analysis of baseline data, showed a non-significant association between higher diet costs and higher HEI scores in children. However, this trial was in a population of children with type 1 diabetes and their parents that were generally high income, and may not be generalizable to the U.S. population.

#### Food expenditures

Seven articles assessed the relationship between the cost of the diet and HEI by measuring food expenditures as the exposure and results from these studies are provided in Table 3-c.^1,4–7,11,12^ Four^4,6,7,12^ out of 7 articles reported that higher food expenditures were significantly associated with higher HEI scores, or that lower food expenditures were significantly associated with lower HEI scores. Two of the 4 articles with significant findings were from the SOS III cohort and contributed unique analyses that answered this question but were from the same population of participants.^6,7^ The 3 other articles found relationships in the same direction but did not reach statistical significance.^1,5,11^

Total food expenditures were generally calculated by summing together expenditures from food at home and food away from home. One of the studies looked at the relationship between all three of these variables and HEI, and saw a positive association with both total and food at home expenditures, but an inverse association with food away from home and HEI.^4^ This means that the total expenditure relationship is being driven by food at home related expenditures. Although this is only 1 study, it is an important consideration when looking at this data.

### Assessment of evidence

As outlined and described below, the body of evidence examining the relationship between diet cost or expenditures and HEI was assessed for the following elements.

#### Risk of bias

Risk of bias assessments for each included article are provided in Table 3-d and Table 3-e. The majority of studies were cross-sectional or cohort studies and did not account for at least 1 key confounder. Many studies had serious concerns with deviations from intended exposures because of using price data that was not specific to what participants paid. Most studies had concerns with missing data and/or the selection of reported results due to the lack of a priori analysis plans or reporting very similar results from the same cohort of participants. One article with non-significant findings had many serious risks of bias for confounding, classification and deviations from intended exposures and outcome measurement due to the fact that they did not adequately describe how the exposure or outcomes were collected or handled and they did not adjust for any confounding factors in the analysis included in this rapid review^1^.

#### Consistency

The direction of the findings were very consistent and the magnitude was consistently small. Most studies reported at least 1 significant association between higher diet cost or expenditures and higher HEI scores. All articles, but one, showed either a significant or non-significant association in a consistent direction, with higher diet cost or expenditures and higher HEI.

#### Directness

There were serious concerns with the directness of exposure measurements. Food expenditure represented purchasing costs that are generally self-reported and are not limited to individual diets. Diet cost is more direct and measures cost of the foods that were consumed but are linked to price databases or sources that were not where the participants actually shopped with a lack of adjustment for geographic location.

#### Precision

There were some concerns with precision across the body of evidence. The effects were relatively consistent with large sample sizes; however, samples may not be large enough to detect small differences in HEI scores.

#### Generalizability

All studies in the body of evidence were conducted in the U.S. and the majority of studies were generalizable to the U.S. population. However, those studies with convenience samples in children with type 1 diabetes and their families, have very limited generalizability. Additionally, multiple studies were completed in the same population of participants (SOS III; HANDLS) and while each contributed unique data, they should not be interpreted as completely independent.

## Summary statements and research recommendations

### Summary statements

The findings of the rapid review are presented in the following summary statements.

##### Diet cost

Evidence suggests a relationship between higher diet costs of foods consumed by participants and higher HEI scores. There were critical limitations including that the prices used were generally not the prices that the participants actually paid, from the same location, or at the same time point as the purchase.

##### Food expenditures

Evidence suggests a relationship between higher total expenditures of food purchases and higher HEI scores. There were critical limitations including that total expenditures were generally self-reported and may not be specific to the foods consumed by the participants.

Total expenditures from food includes both food at home and food away from home. The relationship between total expenditures and HEI scores may be driven by expenditures from food at home, and attenuated by expenditures from food away from home.

### Research recommendations

1. Conduct well-designed longitudinal studies that examine the relationship between diet cost or food expenditures and diet quality over time.
2. Standardize and update national food price databases to increase comparability across studies.
3. Assess diet cost by using prices specific to individuals or standardized national food price databases that are adjusted for participant location and time period of diet data collection.
4. Assess food expenditures that are specific to food at home and food away from home separately, since expenditures from food at home may have a positive relationship with diet quality as where expenditures from food away from home may have an inverse relationship with diet quality.
5. Account for potential confounders to better determine the relationship between diet cost and diet quality.

### Sensitivity Analysis

Articles using data collected prior to 2008 (e.g., 2000-2007; 1999-2005), regardless of publication date, were excluded for this rapid review for the reasons stated in the project methods. However, national price databases are commonly used to determine diet cost, and NESR analysts recognized that articles may not have been included as a result of using the most up to date national data that was available at the time of the authors analyses. A sensitivity anslyses was completed that included articles published in 2008 or later, but that used data from prior to 2008.

There were 5 articles included in the sensitivity analyses, of which 4 found an association between higher diet costs or expenditures and higher HEI scores and were in general agreement with the results of the rapid review.^a^,^b^,^c^,^d^,^e^ All 5 articles used NHANES data and either the CNPP Food Price Database or Consumer Expenditure Survey Data.

a Carlson, A, Dong, D, Lino, M. Are the total daily cost of food and diet quality related: a random effects panel data analysis. 2010.

b Carlson, A, Dong, D.,Lino, M.. Association between Total Diet Cost and Diet Quality Is Limited. Journal of Agricultural and Resource Economics. 2014. 39:47–68

c Carlson, A, Lino, M, Fungwe, TV, Guenther, PM.. Eating a Healthy Diet: Is Cost a Major Factor? 2009.

d Malbi, J, Castner, L, Ohls, J, Fox, MK, Crepinsek, MK, Condon, E. Food Expenditures and Diet Quality Among Low-Income Households and Individuals,” Final Report submitted to USDA, FNS for Contract Number AG-3198-D-07-0114, 2010, http://www.fns.usda.gov/sites/default/files/FoodExpendDietQuality.pdf.

e Rehm, C. D., Monsivais, P., Drewnowski, A.. The quality and monetary value of diets consumed by adults in the United States. Am J Clin Nutr. 2011. 94:1333–9 21918223

Table 3-b Evidence examining the relationship between diet cost and HEI score^a^

Author, Year | Population | Exposure | Outcome | Results
Beydoun, 2015 ^2^; Cross-sectional | Healthy Aging in Neighborhoods of Diversity across the Life Span (HANDLS); Analytic N: 2,111 | Monetary Value of the Diet ($/d); Data source: CNPP Food Prices Database, 2003-2004 (updated for inflation) | HEI-2010 | MVD per $1/d: β=−$1.65 [0.12], p<0.0001; MVD per $3/d: β=−$4.98 [0.35], (IQR: $3.70/d (Q1) to $6.62/d (Q4)), p<0.0001
Beydoun, 2018 ^3^; PCS | Healthy Aging in Neighborhoods of Diversity across the Life Span (HANDLS); Analytic N: 1,466 | Monetary Value of the Diet ($/d); Data source: UNC’s Packaged Food Purchase and Price Database, 2004-2013 | HEI-2010 | T2 v. T1: β=0.71 [0.19] , T3 v. T1: β=1.33 [0.22], p<0.001
Gupta, 2020 ^6^; Cross-sectional | Seattle Obesity Study III (SOS III); Analytic N: 755 | Diet Cost ($/mo); Data source: local retail prices from a large supermarket (i.e. Safeway) | HEI-2015 | Mean HEI (SD): Lowest cost T1 (n=252) 62.57 (9.91) v. middle cost T2 (n=252) 67.18 (9.70) v. highest cost T3 (n=251) 71.55 (7.87), p<0.0001
Gupta, 2021 ^7^; Cross-sectional | Seattle Obesity Study III (SOS III); Analytic N: 747 | Diet Cost ($/mo); Data source: local retail prices from a large supermarket (i.e. Safeway) | HEI-2015 | Mean HEI (SD): ≤$252: 62.6 (10) (ref) v. >$253–≤$299: 67.1 (9.77), p<0.0001 v. ≥$300: 71.5 (7.81), p<0.0001
Rose, 2020 ^11^; Cross-sectional | Seattle Obesity Study III (SOS III); Analytic N: 768 | Diet Cost ($/mo); Data source: local retail prices from a large supermarket (i.e. Safeway) | HEI-2015 | Linear models:; Mean HEI per $100: 5.33, 95% CI: 4.15, 6.50, p<0.0001; Curvilinear models:; 17.82, 95% CI: 9.76, 25.88, p<0.0001; Quadratic model: −2.06, 95% CI: −3.35, −0.78, p<0.0002
Rehm, 2015 ^10^; Cross-sectional | NHANES; Analytic N:11,181 | Diet Cost ($/mo); Data source: CNPP Food Prices Database, 2003-2004 (updated for inflation) | HEI-2010 | Q1, n = 2545: 44.2, 95% CI: 42.7, 45.7 (ref); Q2, n = 2348: 50.1, 95% CI: 48.7, 51.5, p<0.001; Q3, n = 2231: 55.8, 95% CI: 54.1, 57.6, p<0.001; Q4, n = 2073: 60.2, 95% CI: 58.2, 62.1, p<0.001; Q5, n = 1984: 66.6, 95% CI: 65.3, 67.9, p<0.001
Nansel, 2015 ^8^; Cross-sectional (baseline data from RCT) | Youth with Type 1 Diabetes; Analytic N: 252 | Diet Cost ($/d); Data source: National online supermarket prices | HEI-2005 | Mean HEI (SD): T1 (lowest) $6.67 [0.37] v. T2 $6.80 [0.36] v. T3 $7.35 [0.37], p-trend=0.20, NS
Nansel, 2016 ^9^; RCT | Youth with Type 1 Diabetes and their parents; Analytic N: 136 | Diet Cost ($/d); Data source: National online supermarket prices | HEI-2005 | Youth: β=−0.0005, 95% CI: −0.02, 0.02, p=0.96, NS;; Adults: β=−0.06, 95% CI: −0.13, 0.01, p=0.11, NS

a Abbreviations: CNPP, Center for Nutrition Policy and Promotion; d, day; HEI, healthy eating index; HANDLS, Healthy Aging in Neighborhoods of Diversity across the Life Span; HH, household; mo, month; NS, not significant; PCS, prospective cohort study; RCT, randomized controlled trial; SOS III, Seattle Obesity Study III

Table 3-c Evidence examining the relationship between food expenditures and HEI scores^a^

| Population | Exposure | Outcome | Results
Carpio, 2020^4^; Cross-sectional | Staff and Faculty at Public University in West Texas; Analytic N: 142 | Weekly food expenditures ($/wk; HH); Diet source: self report | HEI-2015 | Total food expenditures: β=0.058 [0.03], p<0.10;; Food at home expenditures (natural log): β=0.085 [0.029], p<0.01;; Food away-from-home expenditures (natural log): Coefficient −0.002 [0.010], NS;
Sanjeevi, 2018^12^; PCS | Low-income women in Texas; Analytic N: 144 | Food expenditures relative to TFP cost ($/mo; per capita); Diet source: monthly grocery receipts | HEI-2010 | β=5.29, SE: 2.60, p=0.04
Gupta, 2020^6^; Cross-sectional | Seattle Obesity Study III; Analytic N: 755 | Food expenditures ($/mo; per capita); Diet source: self report | HEI-2015 | Mean HEI (SD): Lowest expenditure T1 65.23 (9.53) v. middle expenditure T2 (n=271) 66.80 (10.04) v. highest expenditure T3 (n=232) 69.45 (9.68), p<0.0001
Gupta, 2021^7^; Cross-sectional | Seattle Obesity Study III; Analytic N: 747 | Food expenditures at home ($/mo; per capita); Diet source: self-report | HEI-2015 | Mean HEI (SD): ≤$100: 65.2 (9.96) (ref) v. >$100–≤$175: 66.4 (9.88), p=0.177 v. ≥$175: 69.9 (9.27), p=0.0001;
Rose, 2020^11^; Cross-sectional | Seattle Obesity Study III; Analytic N: 768 | Food expenditures at home ($/mo; per capita); Diet source: self report | HEI-2015 | Linear model, Mean HEI per $100: 0.09, 95% CI: −0.49, 0.67, NS; Curvilinear model, NR, NS
Anderson, 2016^1^; Cross-sectional | NHANES; SNAP participants; Analytic N: NR | Grocery Spending (per capita); Diet source: NR | HEI (unspecified) | β=0.004 (0.004), NS
Dubowitz, 2015^5^; Cross-sectional | PHRESH: majority African-American population near Pittsburgh; Analytic N: 1,372 | Weekly food expenditures ($/wk; per capita); Diet source: self-report | HEI-2005 | β=0.004; NS

a Abbreviations: HEI, healthy eating index; HH, household; mo, month; NHANES, National Health and Nutrition Examination Survey; PCS, prospective cohort study; PHRESH, Pittsburgh Hill/Homewood Research on Neighborhood Change and Health; NR, not reported; NS, not significant; RCT, randomized controlled trial; wk, week

Table 3-d Risk of bias for the randomized controlled trial examining diet cost or expenditures and HEI^a^

Article | Randomization | Deviations from intended interventions (effect of assignment) and (per-protocol) | Missing outcome data | Outcome measurement | Selection of the reported result
Nansel, 2016^9^ | LOW | SOME CONCERNS | SOME CONCERNS | LOW | SOME CONCERNS

a Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2016 version)” (Higgins JPT, Sterne JAC, Savović J, Page MJ, Hróbjartsson A, Boutron I, Reeves B, Eldridge S. A revised tool for assessing risk of bias in randomized trials In: Chandler J, McKenzie J, Boutron I, Welch V (editors). Cochrane Methods. Cochrane Database of Systematic Reviews 2016, Issue 10 (Suppl 1). 10.1002/14651858.CD201601.)

Table 3-e Risk of bias for observational studies examining diet cost or expenditures and HEI^a^

Article | Confounding | Selection of participants | Classification of exposures | Deviations from intended exposures | Missing data | Outcome measurement | Selection of the reported result
Anderson, 2016^1^ | SERIOUS | LOW | SERIOUS | SERIOUS | NI | SERIOUS | MODERATE
Beydoun, 2018^3^ | LOW | MODERATE | MODERATE | SERIOUS | MODERATE | LOW | MODERATE
Beydoun, 2015^2^ | LOW | MODERATE | SERIOUS | SERIOUS | MODERATE | LOW | MODERATE
Carpio, 2020^4^ | SERIOUS | SERIOUS | MODERATE | SERIOUS | MODERATE | LOW | MODERATE
Dubowitz, 2015^5^ | MODERATE | MODERATE | LOW | LOW | MODERATE | LOW | MODERATE
Gupta, 2020^6^ | SERIOUS | MODERATE | LOW | MODERATE | MODERATE | LOW | SERIOUS
Gupta, 2021^7^ | LOW | MODERATE | LOW | MODERATE | MODERATE | LOW | SERIOUS
Nansel, 2015^8^ | SERIOUS | SERIOUS | LOW | MODERATE | MODERATE | LOW | MODERATE
Rehm, 2015^10^ | MODERATE | LOW | LOW | SERIOUS | LOW | LOW | LOW
Rose, 2020^11^ | LOW | MODERATE | LOW | MODERATE | MODERATE | LOW | SERIOUS
Sanjeevi, 2018^12^ | SERIOUS | MODERATE | MODERATE | LOW | LOW | LOW | LOW

a Possible ratings of low, moderate, serious, critical, or no information determined using the “Risk of Bias for Nutrition Observational Studies” tool (RoB-NObs) ( Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC. )

## References of the articles included in the diet cost and HEI rapid review

1 Anderson PM, Butcher KF. The Relationships Among SNAP Benefits, Grocery Spending, Diet Quality, and the Adequacy of Low-Income Families’ Resources. Center on Budget and Policy Priorities. 2016.
2 Beydoun MA, Fanelli-Kuczmarski MT, Allen A, . Monetary Value of Diet Is Associated with Dietary Quality and Nutrient Adequacy among Urban Adults, Differentially by Sex, Race and Poverty Status. PLoS One. 2015;10(11):e0140905 doi:10.1371/journal.pone.0140905. eCollection 2015.26536243
3 Beydoun MA, Fanelli-Kuczmarski MT, Poti J, . Longitudinal change in the diet’s monetary value is associated with its change in quality and micronutrient adequacy among urban adults. PLoS One. 2018;13(10):e0204141 doi:10.1371/journal.pone.0204141. eCollection 2018.30312298
4 Carpio CE, Kalenkoski CM, Moyeda-Carabaza AF, Murimi M. The effect of time use and food cost on dietary quality. Public Health Nutr. 2020;23(18):3284–3294 doi:10.1017/S1368980020001615. Epub 2020 Jul 13.32657264
5 Dubowitz T, Zenk SN, Ghosh-Dastidar B, . Healthy food access for urban food desert residents: examination of the food environment, food purchasing practices, diet and BMI. Public Health Nutr. 2015;18(12):2220–2230 doi:10.1017/S1368980014002742. Epub 2014 Dec 5.25475559
6 Gupta S, Rose CM, Buszkiewicz J, . Characterising percentage energy from ultra-processed foods by participant demographics, diet quality and diet cost: findings from the Seattle Obesity Study (SOS) III. Br J Nutr. 2020:1–9 doi:10.1017/S0007114520004705.
7 Gupta S, Rose CM, Buszkiewicz J, Otten J, Spiker ML, Drewnowski A. Inedible Food Waste Linked to Diet Quality and Food Spending in the Seattle Obesity Study SOS III. Nutrients. 2021;13(2) doi:10.3390/nu13020479.
8 Nansel T, Haynie D, Lipsky L, Mehta S, Laffel L. Little variation in diet cost across wide ranges of overall dietary quality among youth with type 1 diabetes. J Acad Nutr Diet. 2015;115(3):433–439 e431 doi:10.1016/j.jand.2014.07.035. Epub 2014 Sep 27.25266245
9 Nansel TR, Lipsky LM, Eisenberg MH, Liu A, Mehta SN, Laffel LM. Can Families Eat Better Without Spending More? Improving Diet Quality Does Not Increase Diet Cost in a Randomized Clinical Trial among Youth with Type 1 Diabetes and Their Parents. J Acad Nutr Diet. 2016;116(11):1751–1759 e1751 doi:10.1016/j.jand.2016.07.005. Epub 2016 Aug 31.27597745
10 Rehm CD, Monsivais P, Drewnowski A. Relation between diet cost and Healthy Eating Index 2010 scores among adults in the United States 2007-2010. Prev Med. 2015;73:70–75 doi:10.1016/j.ypmed.2015.01.019. Epub 2015 Jan 24.25625693
11 Rose CM, Gupta S, Buszkiewicz J, . Small increments in diet cost can improve compliance with the Dietary Guidelines for Americans. Soc Sci Med. 2020;266:113359 doi:10.1016/j.socscimed.2020.113359. Epub 2020 Sep 11.32949981
12 Sanjeevi N, Freeland-Graves JH. Association of Grocery Expenditure Relative to Thrifty Food Plan Cost with Diet Quality of Women Participating in the Supplemental Nutrition Assistance Program. J Acad Nutr Diet. 2018;118(12):2315–2323 doi:10.1016/j.jand.2018.07.015. Epub 2018 Sep 28.30270030