# Chapter 2 What is the relationship between income or Federal Assistance participation/eligibility and following a dietary pattern that aligns with the Dietary Guidelines for Americans, as measured by the Healthy Eating Index (HEI)?

## Specific methods to conduct this rapid review

### Develop a protocol

The research question, “What is the relationship between income and HEI?”, was answered using a rapid review that was informed by an evidence scan.

The analytic framework for the rapid review examining the relationship between income and following a dietary pattern that aligns with the Dietary Guidelines for Americans, as measured by the Healthy Eating Index (HEI), is presented in Figure 2-a. This analytic framework visually represents the overall scope of the rapid review question and depicts the contributing elements that were examined and evaluated. The intervention or exposure of interest is income or Federal assistance participation/eligibility in Americans. The comparators are different levels or categories of income or participation/eligibility status. The outcomes are HEI scores in Americans. The key confounders are urban versus rural settings, cultural/racial diversity or disparities, sex, age, food security status. The other factors to be considered are cultural food choices, neighborhood characteristics (e.g., access to food/distance to stores/access to car/type of store), smoking, weight status, chronic disease status, convenience level, and processing level. The confounders and other factors to be considered may impact the relationships of interest.

An evidence scan was conducted before the rapid review, and it included additional intervention/exposures of income proxies including socioeconomic status (SES) factors such as education, marital status, or household assets, food security status, and geographical areas. Based on the evidence scan, the intervention/exposure for the rapid review was narrowed to include only income or Federal assistance participation/eligibility in Americans to produce the strongest body of evidence that would be of most utility for the Thrifty Food Plan, 2021. The evidence scan also included outcomes of either consumption or purchasing of dietary patterns, diet diversity, and other diet quality indicators/scores as the outcomes, regardless of approach or measure used to study the dietary pattern. The outcome for the rapid review was narrowed to include only HEI scores based on consumption as these were by far the most common outcome studied across the evidence scan and the NEAT staff recognized that additional information would not be useful for the Thrifty Food Plan, 2012 by the inclusion of other types of dietary patterns that were not in direct alignment with the Dietary Guidelines for Americans. Comparisons of Federal assistance benefits between states were considered in the scan, but excluded from the rapid review for lack of applicability to the entire U.S. population. Similarly, comparisons of temporality within receipt month of Federal assistance benefits (e.g., 15 days past receipt v. 30 days past receipt) were considered in the scan, but excluded from the rapid review for lack of directness to the intended exposure of income.

Figure 2-a Analytic Framework for the rapid review on income and HEI

### Search for and select studies

The following outlines any departures from the search and select studies project methods for this specific rapid review:

- 80% of all records were single-screened at title, abstract, and full-text levels and 20% of all records were dual-screened, independently at each of these levels.

NESR analysts worked jointly with NEAT staff to establish the final inclusion and exclusion criteria and literature search strategy, which are detailed in Table 2-a and Appendix 2-a, respectively.

Table 2-a Inclusion and exclusion criteria for the rapid review on income and HEI

Category | Inclusion Criteria | Exclusion Criteria
Study design | - Any study design that is not a narrative review, systematic review, or meta-analysis | - Narrative reviews; - Systematic reviews; - Meta-analyses
Intervention/exposure | - Income (e.g., household, city, regional income); - Income-based Federal assistance program participation/eligibility | - Other proxies used for income
Comparator | - Different levels or categories of income; - Different participation/eligibility status in income-based Federal assistance program(s) | - Comparison of geographic areas without a proxy for income
Outcomes | - Dietary patterns that specifically align with the Dietary Guidelines for Americans, as measured by the total Healthy Eating Index (HEI); - All versions or variations of HEI (e.g. HEI-2005, HEI-2010, HEI-2015); - Change in total HEI over time | - Studies that examine any other dietary pattern or diet quality indicator that include only individual or select foods and beverages and do not reflect the totality of the diet nor the Dietary Guidelines for Americans.; - Studies that only examine component scores of the HEI
Publication date | - Jan 2008 - May 2021 and data inclusive of 2008 (e.g., 2000-2012; 2008-2009) | - Articles published prior to Jan 2008; - Data prior to 2008 (e.g., 2000-2007; 1999-2005)
Publication status | - Articles that have been peer-reviewed; - Grey literature: reports that have not been peer reviewed but are available from government and nongovernmental organizations | - Articles that have not been peer reviewed and are not published in peer-reviewed journals (e.g., unpublished data, manuscripts, pre-prints, reports, abstracts, and conference proceedings), other than reports from government and nongovernmental organizations
Language | - Articles published in English | - Articles published in languages other than English
Country | - Studies conducted in the U.S. | - Studies conducted outside the U.S.
Study participants | - Human participants/populations | - Non-human participants (e.g., animal studies, in-vitro models)
Age of study participants | - Age at intervention or exposure:; ○ Infants and toddlers (birth to 24 months); ○ Children and adolescents (2-18 years); ○ Adults (19-64 years); ○ Older adults (65 years and older); - Age at outcome:; ○ Infants and toddlers (birth to 24 months); ○ Children and adolescents (2-18 years); ○ Adults (19-64 years); ○ Older adults (65 years and older)

### Extract data and assess the risk of bias

NESR analysts extracted and summarized data from each included article to objectively describe the body of evidence available to answer a rapid review question. The following outlines any departures from the extract data and assesses risk of bias project methods for this specific rapid review:

- Data extraction and risk of bias assessment was completed on all included articles and verified by a 2^nd^ analyst

### Synthesize the evidence

Evidence synthesis was completed by describing the evidence and evaluating the included studies individually and collectively as previously described in the project methods.

### Summary statements

NESR analysts formed summary statements, as previously described in the project methods, outlining the themes observed during the data synthesis of studies examining income and HEI.

### Recommend future research

Recommendations for future research evaluating the relationship between income and HEI were determined based on the gaps and limitations observed during data extraction and synthesis, as previously described in the project methods. Future work addressing these gaps and limitations may contribute to the body of evidence available to answer this research question.

## Results

### Literature search and screening results

The literature search yielded 10,692 search results after the removal of duplicates (see Figure 2-b). Dual-screening resulted in the exclusion of 9,719 titles, 646 abstracts, and 183 full-texts articles. Reasons for full-text exclusion are in Appendix 2-b. Five additional articles were identified from the manual search. The body of evidence for the rapid review included 61 articles.

Figure 2-b Literature search and screen flowchart for the rapid review on income and HEI

### Description of evidence

This rapid review included 61 articles that examined the relationship between income and HEI. Four articles came from prospective cohort studies^1–4^ and the rest (57 articles) were from cross-sectional study designs.^5–61^ Common data sources of these studies included the National Health and Nutrition Examination Survey (NHANES)^5,13,14,23,24,26,29,33,37–44,47–49,52–54,56,61^ and the Continuing Survey of Food Intake by Individuals (CSFII).^7,45^ Four articles were included from the Healthy Aging in Neighborhoods of Diversity across the Life Span Study (HANDLS) but represented unique data by examining different sub-samples or analytic/assessment methods.^1,6,9,34^

#### Population characteristics

Most of the studies (~41%) were conducted using data from national databases or by enrolling participants from multiple states, with a few select studies conducted exclusively in rural or urban cities or areas. Across the body of evidence, analytic sample sizes ranged from n=80 to n=43,996. More information on the location and analytic sample size from each individual article can be found in Table 2-b.

Studies varied across all populations and life stages. Most of the studies examined data in adults^1,2,5–7,9–12,15–18,20,25,28,30,31,34,37,41–46,48–51,54,56–58,60,61^ with a smaller sub-set of articles examining data in children (toddlers through adolescents).^4,8,14,19,21,24,26,27,29,32,33,35,38–40,52,53^ In addition, there were 7 articles that studied children and adults^13,47^, or child-adult dyads.^3,22,36,55,59^ One study examined household data.^23^

Most studies enrolled participants regardless of sex, although select studies enrolled only women^50^, or those who were pregnant.^16,28,51^ Most studies enrolled participants regardless of racial/ethnic background, but select studies enrolled only those who were Hispanic,^51,61^ of Mexican-origin,^40^ African-American,^46,50^ Haitian-American,^30^ or members of the Confederated Salish, Pend d’Oreille, or Kootenai tribes of Flathead nation.^10^ Select studies exclusively enrolled participants with diagnosed diabetes^12,44^ or cancer.^31^

#### Exposure and comparator characteristics

Studies examined household income^8,10,11,15–18,20,22,30,36,46,50,58,60^ or poverty (e.g., poverty-to-income ratio (PIR)).^1,3–5,7,9,12,34,40,43–45,48,52,53,61^. Studies varied in the cut-off points used for income, poverty, or thresholds applied, whether or not household/family size was accounted for in the income variable, and/or percentage of residents in living poverty at that address according to Census data.

Both income or poverty and Federal assistance program participation/eligibility were examined in a subset of studies.^24–26,28,31–33,39,55,59^

Studies examined participation and eligibility in various Federal assistance programs,^2,6,13,14,19,21,23,25–33,35,37–39,41,42,47,49,51,52,54–57,59^ including Supplemental Nutrition Assistance Program (SNAP, formerly Food Stamps) eligibility and participation,^2,6,13,23–25,28,29,31,35,37–39,41,42,47,49,54,56,57^ National School Lunch Program (NSLP) or School Breakfast Program (SBP) participation,^14,19,21,24,26,27,33,39^ Supplemental Assistance Program for Women, Infants and Children (WIC) participation and duration,^25,32,39,51,59^ and other programs (e.g., Child and Adult Care Food Program (CACFP),^55^ and Medicaid or Supplemental Security Income (SSI)^25,31^).

#### Outcome assessment

All studies examined dietary patterns aligned with the DGA as measured by the HEI^22^, HEI-2005 (14 articles)^7,12–15,18,23,26,30,36–38,56,58^, HEI-2010 (31 articles) ^1,2,4–6,9–11,17,19–21,24,25,27–29,31–34,40–44,46,50,54,60,61^, and/or HEI-2015 (15 articles)^3,8,16,35,39,45,47–49,51–53,55,57,59^. Scores on the HEI were determined using a variety of dietary assessment methods, including food frequency questionnaires or 24-hour dietary recalls.

### Synthesis

Results from all included studies are provided in Table 2-b. Income was significantly associated with HEI scores in 20 articles.^1,3–7,9,13,20,22,30,36,40–44,48,49,54^ Results were reported as lower income/greater poverty associating with lower HEI scores, higher income/less poverty associating with higher HEI scores, and/or as participation versus non-participation in Federal assistance program(s) associating with lower HEI scores.

Eleven articles reported ‘positive’ associations (that is, higher income associated with higher HEI scores) with not all results reported reaching statistical significance.^2,17,23,25,26,33,37,39,45,50,58^ Five articles^14,21,19,24,59^ reported at least 1 significant ‘inverse’ association with 3 finding that NSLP participants (compared to non-participants) had significantly higher HEI scores.^14,19,21^ Gu et al^24^ reported that NSLP was significantly associated with lower HEI scores and WIC participation was significantly associated with higher HEI scores, but comparisons based on income or SNAP status were not significant. Weinfield et al^59^ similarly reported that longer WIC duration was significantly associated with higher HEI scores, but comparisons of HEI by poverty were not significant.

The remaining articles reported no significant association between income,^8,10,11,15,16,18,31,32,46,55,60^ poverty-to-income ratio,^12,34,52,53,61^ Federal assistance participation/eligibility/duration (SNAP,^29,35,38,47,51,56,57^ NSLP,^27^ WIC,^51^), or both income and Federal assistance^28^ and HEI scores.

### Assessment of evidence

As outlined and described below, the body of evidence examining the relationship between income and HEI was assessed for the following elements.

#### Risk of bias

Risk of bias assessments for each included article are provided in Table 2-c. The preponderance of evidence came from observational studies, particularly cross-sectional data or design, that did not account or adjust for key confounders including food insecurity/hunger and urban/rural setting. Many studies had serious or some concerns with classification of income due to self-selection of Federal assistance program participation/eligibility status and/or proxy calculations. Many studies had serious concerns related to comparisons with little difference between income levels of exposure groups or likelihood that participants’ income or Federal participation/eligibility status was assessed at a single point in time but likely instable. Many studies also had concerns with missing data and/or the selection of reported results due to the lack of a priori analysis plans/protocol.

#### Consistency

The direction of findings consistently showed that lower income was associated with lower HEI scores and the magnitude of the effect was consistently small, with many reported results not reaching statistical significance. Participation in Federal assistance programs was correlated with lower diet quality, as measured by HEI scores. However, about half of the articles found no statistically significant relationships between income and HEI.

#### Directness

The body of evidence had several concerns regarding directness, particularly the exposures and/or comparators examined by studies were not directly related to the question of interest. For example, studies examining SNAP participation tended to compare groups that had similar or nearly similar income levels. In addition, the population in several articles were all low-income or all participants in specific Federal assistance programs. Outcomes examined in all studies were directly related to the question.

#### Precision

Several concerns with precision were identified across the body of evidence. Although sample sizes were relatively large, the reported effects tended to be small in magnitude (of little practical/clinical significance) and have wider confidence intervals indicating limited precision.

#### Generalizability

Although all studies were conducted in the U.S. and many used nationally representative data, the generalizability was limited in several studies particularly related to the selection of participants. For example, several studies examined differences within exclusive populations such as all WIC participants, all low-income participants, only Mexican-origin children, or only Haitian-Americans.

## Summary statements and research recommendations

### Summary statements

The findings of the rapid review are presented in the following summary statement[s].

Evidence suggests lower income or greater poverty is correlated with lower HEI scores. Critical limitations in the design and conduct of most included studies were identified that impact the validity of the reported results. In addition, the findings that reached statistical significance tended to lack meaningful clinical/practical significance (e.g., 1 to 5 point higher HEI scores) but remaining within a range of needing improvement.

Studies widely varied in how they defined and examined income exposures. No clear trends were found between studies that examined similar or different income groupings.

Studies that examined Federal assistance eligibility/participation often reported indirect income exposures or comparisons, and/or treated income constant between participant groups.

Relatively few studies accounted for food security/hunger. No clear trends were found among exposures, outcomes, or significance of results based on whether food security was accounted for or not.

### Research recommendations

1. Conduct well-designed, longitudinal studies that examine the relationship between income and diet quality over time.
2. Assess income exposures using standard definitions and categories to improve comparability across studies.
3. Differentiate between participants in studies who are income-eligible, income-eligible nonparticipants, and income-ineligible nonparticipants of Federal assistance programs.
4. Account for hunger or food security status of participants, as well as other potential confounders including urban/rural setting and cultural/racial diversity or disparities, to better determine the response to income on dietary patterns as a function of these factors.

Table 2-b Evidence examining the relationship between income and/or Federal assistance participation/eligibility and HEI^a^

Article^*^; * All study designs and/or data reported were cross-sectional unless indicated by *PCS, which indicates a prospective cohort study design. | N | Population | Exposure | Outcome | Results^†^; † Unless otherwise noted, results are formatted as mean (SD), mean [SE], odds ratio (OR), relative risk (RR), and/or 95% Confidence Interval (CI). Results that were statistically significant are bolded and those that were not statistically significant are indicated either by the respective p value or NS. | Summary of Limitations
Income
Bekelman, 2021^8^ | 482 | Children, 5 y; Colorado; [underlined: Data source:] Healthy Start study | Income: <$75K v. ≥ $75K | HEI-2015 | OR: 0.84, 95% CI: 0.54, 1.31, NS | Did not account for confounders of: Urban vs. Rural; Food security; Some concerns with departure from intended exposure due to lack of accounting for food insecurity/hunger
Byker Shanks, 2020^10^ | 80 | Adults, ≥18 y; Flathead nation, Montana; [underlined: Data source:] N/A | Income, $ | HEI-2010 | data NR, p< 0.21; NS | Minimal concerns with selection into study and selection of reported results
Chen, 2018^11^ | 298 | Adults: Parents of children, 9 to 10 y; rural Texas; [underlined: Data source:] Student Wellness Assessment and Advocacy Project [SWAAP] | Income: Low <$40K; Medium $40,001–$70K; High >$70,001 | HEI-2010 adapted | β= 0.09, r=−0.29189, p=0.268; NS | Did not account for confounders of: Food security; Some concerns with outcome measurement due to adaption of HEI-2010
Deierlein, 2014^15^ | 1306 | Adults, 60 to 99 y; New York City, New York; [underlined: Data source:] Cardiovascular Health of Seniors and the Built Environment Study | Annual HH income: > $30K (ref) v. ≤ $30K | HEI-2005 | HEI ≥ 80 v. <80 RR: 1.20 95% CI: 0.93, 1.55 | Some concerns with selection bias; Some concerns with departure from intended exposure
Deierlein, 2021^16^ | 1016 | Adults, all pregnant women, ≥ 18 y[underlined: ;] New York City, New York; [underlined: Data source:] New York University Children’s Health and Environment Study (NYU CHES) | Income: <$30K; $80K-$99.999K; ≥$100K | HEI-2015 | ≥$100k (ref) v. <$30k: 1.92, 95% CI: −0.41, 4.25, NS; ≥$100k (ref) v. $30-$99.999k: 1.02, 95% CI: −0.53, 2.57, NS | Did not account for confounders of: Food security; Some concerns with selection bias; Some concerns with departure from intended exposure related to potential for changes from timing of assessments; Limited generalizability to non-pregnant populations
Drewnowski, 2016^17^ | 1116 | Adults, ≥ 18 y[underlined: ;] Seattle, Washington; [underlined: Data source:] Seattle Obesity Study (SOS) | Income, ≤$50K ref v.$50K to < 100K; ≤$50K ref v.≥$100K | HEI-2010; HEI-2005 | HEI-2010:; $50K to <100K: 1.34, 95% CI: −0.13, 2.82; ≥$100K: 2.57, 95% CI: 0.96, 4.19; HEI-2005:; $50K to <100K: 0.72, 95% CI: −0.73, 2.19; NS; ≥$100K: 1.30, 95% CI: −0.28, 2.89; NS | Did not account for confounders of: Food security; Some concerns with departure from intended exposure
Flórez, 2015^18^ | 639 | Adults, ≥ 18 y, all SNAP participants[underlined: ;] Pennsylvania; [underlined: Data source:] Pittsburgh Hill/Homewood Research on Eating, Shopping and Health (PHRESH) study | Adjusted annual HH income ≥ $10K | HEI-2005 | β= −0.0235, p=0.6787; NS | Some concerns with departure from intended exposure, missing data, outcome measurement and reported results; Limited generalizability to non-SNAP participants
Freedman, 2019^20^ | 101 | Adults, 19 to 92 y, living in urban food desert; Ohio; [underlined: Data source:] BRFSS | Annual HH Income | HEI-2010 | Path modeling including the collective influence of individual, social, and built food environment factors on diet quality with income included in the models:; Cleveland: Income, β= 0.171, p<0.05; Columbus: Income, β=0.300, p<0.10 | Some concerns with classification of exposure and departure from intended exposure; Concerns with indirectness
Gibbs, 2016^22^ | 177 | Dyads of Children 4 to 6 y, with parents (primary food purchaser/preparer); Kansas; [underlined: Data source:] Kansas University Docosahexaenoic Acid Outcomes Study (RCT); Nutrition Literacy Assessment Instrument for Parents (NLit-P) | HH income, $, mean | HEI | Income: r=0.218, p <0.05 | Did not account for confounders of: Urban vs. Rural; Food security
Laster, 2013^36^ | 113 | Dyads of Overweight/obese (BMI≥25), 2-7 mo post-partum mothers, ≥18 y and their preschooler, 2 to 5 y; North Carolina; [underlined: Data source:] Kids and Adults Now!—Defeat Obesity (KAN-DO) | HH income, up to $15K $15001-$30K, $30001-$60K, ≥$60001 | HEI-2005 | Mother HH income: <$15K 59.5 (9), $15001-$30000, 65.9 (11), $30001-$60K, 66.4 (10.5), ≥$60K, 70.3 (8.7), p<0.0001; Stepwise model predicting child HEI: $15K v. >$15K, β=−2.33 [1.10], p=0.04; $15001 to $60K v. ≥$60K,1 β=−1.73 [0.72], p=0.02 | Did not account for confounders of: Urban vs. Rural; Food security; Some concerns with classification of exposures due to proxy with caretakers
Huffman, 2014^30^ | 487 | Adults ≥35 y, Haitian-Americans without diabetes; Florida; [underlined: Data source:] NR | <$20K/y v. ≥ $20K/y | HEI-2005 | β=−5.30, 95% CI: 0.03, −10.6, p=0.051 | Did not account for confounders of: Urban vs. Rural; Food security; Some concerns with selection into study, departure from intended exposures, and reported results. Limited generalizability related to studying only Haitian-American immigrants.
Richards Adams, 2019^46^ | 100 | Adults, 18 to 74 y, African American living in a metropolitan area[underlined: ;] Kentucky; [underlined: Data source:] N/A | Income | HEI-2010 | Bivariate correlation r=0.13, NS; Linear regression β=0.10, p=0.82, NS | Did not account for confounders of: Food security; Some concerns with selection into study; Limited due to convenience sample
Springfield, 2019^50^ | 210 | Adults, all women, African-American, previous breast cancer, and interested in weight-loss (all overweight or obese)[underlined: ;] Chicago, IL; [underlined: Data source:] Moving forward study, a RCT for weight loss self-selecting into study for weight loss | Income, $ | HEI-2010 | β=1.44 [0.52], p≤ 0.01, but did not move forward in adjusted models | Did not account for confounders of: Urban vs. Rural; Food security; Some concerns with selection into study; Limited generalizability due to participants self-selecting into study for weight loss
Weatherspoon, 2017^58^ | 2687 | Adults, ≥ 19 y[underlined: ;] Michigan; [underlined: Data source:] Michigan State University Extension (MSUE) | HH income $100 and $500/pp/mo v. <$100/pp/mo | HEI-2005 | Δ HEI exit-entry after SNAP-Ed only: −0.68 [0.02], p<0.01; Δ HEI exit-entry after EFNEP only: −0.85 [0.03], p<0.01; Data NR: HH income $100 and $500/pp/mo v. <$100/pp/mo increased in ΔHEI scores, p<0.05; $500 or more, NS | Did not account for confounders of: Food security; Serious concerns with departure from intended exposures; Comparator not directly related to question of interest
Wilcox, 2020^60^ | 465 | Adults, ≥18 y, shoppers for ≥50% household’s food[underlined: ;] South Carolina cities; [underlined: Data source:] N/A | Income: <$10k; $10-$19.999k; ≥$20k | HEI-2010 | <$10k: 47.42 v. $10-$19.999k: 47.26 v. ≥$20k: 49.75, NS; Income, F (4, 448)=6.71, p<0.001, r2=0.06; F(2, 448)=1.29, p=0.28 | Did not account for confounders of: Cultural/racial diversity or disparities; Food security; Serious concerns with departure from intended exposures
Poverty
Aggarwal, 2016^5^ | 8957 | Adults, ≥20 y; National dataset; [underlined: Data source:] NHANES, 2007-2010 | FIPR: family income-to-poverty ratio, adjusted for HH size | HEI-2010 | FIPR <130%: 45.6, 131-184%: 47.1, 185-399%: 48.4, ≥400%: 51.7; <130% (ref) v. 131-184%: 1.96 [0.86], p=0.030; <130% (ref) v. 185-399%: 3.21 [0.50], p<0.001; <130% (ref) v. ≥400%: 6.48 [0.60], p<0.001 | Did not account for confounders of: Urban vs. Rural; Food security; Some concerns due to missing data
Beatty, 2014^7^ | 37263 | Adults, ≥ 20 y; National dataset; [underlined: Data source:] CSFII, 1989-1991, 1994-1996; NHANES, 2001-2008 | HH Income <185% FPG (low) | HEI-2005 | 2005-2008, n=9258: low-income 51.37 (14.99), 95% CI: 8.78, 94.60 v. higher-income 52.92 (11.29), 95% CI: 10.00, 95.38, p<0.05; Data NR (in figures): For HEI below 45, higher-income individuals experienced a greater improvement over the period 1989–2008 than low-income individuals. Whereas at higher levels of the HEI distribution, low-income individuals experienced greater increases in HEI. | Did not account for confounders of: Urban vs. Rural; Food security; Some concerns with departure from intended exposure due to lack of accounting for food insecurity/hunger; Some concerns with outcome measurement due to timing of dietary data collected vs.. calculated; Some concerns with reported results; Limitations related to date range of data collected
Beydoun, 2015^9^ | 2111 | Adults, 30 to 64 y; Baltimore, Maryland; [underlined: Data source:] Healthy Aging in Neighborhoods of Diversity across the Life Span Study (HANDLS) | PIR: ≥ 125% poverty threshold v <125% poverty threshold | HEI-2010 | PIR≥125%: 43.82 (0.35) v. <125%: 40.93 (0.34), p<0.05 | Did not account for confounders of: Sex; Age; Food security; Some concerns with departure from intended exposure due to lack of accounting for food insecurity/hunger; Some concerns with outcome measurement
Beydoun, 2018^1^ *PCS | 1466 | Adults, 30 to 64 y; urban Maryland; [underlined: Data source:] HANDLS | PIR <125% poverty threshold, ≥125% poverty threshold | HEI-2010 | baseline, ≥125%, 44.5 [0.4] v. <125%, 41.3 [0.4], p<0.001; follow-up, ≥125%, 47.95 [0.4] v.<125%, 44.6 [0.46], p<0.001; change, ≥125%, +0.78 [0.10] v. <125%, +0.68 [0.10], NS | Did not account for confounders of: Food security; Some concerns with selection bias; Some concerns with departure from intended exposure due to lack of accounting for food insecurity/hunger; Some concerns with reported results due to no protocol
Coltman, 2013^12^ | 99 | Adults, 18 to 75 y; diagnosed with type 2 diabetes[underlined: ;] urban Illinois; [underlined: Data source:] N/A | PIR ≤130%, >130%, based on # of people living in HH | HEI-2005 | PIR: ≤130%, 56.0 (11.3) v. >130%, 56.6 (9.6); NS; Correlations with HEI: PIR: −0.075; NS | Critical concerns due to not accounting for confounders of: Cultural/racial diversity or disparities; Sex; Age; Food security; Serious concerns due to selection into study based on diabetic status; Some concerns with departure from intended exposure; Limited generalizability
Covington, 2020^3^ *PCS | 207 | Dyads of Children, 12 to 32 mo with their mothers; Mid-Atlantic region; [underlined: Data source:] NCT02615158 | Poverty based on parent-reported income and family size, <1.0 indicated below poverty threshold | HEI-2010 | Between-person indirect effect: 3.797 [0.842], 95% CI: 2.133, 5.460, p<0.05; Within-person indirect effect: −3.552 [2.230], 95% CI: −7.948, 0.844, NS | Did not account for confounders of: Cultural/racial diversity or disparities (68% Non-Hispanic Black); Food security; Some concerns due to missing data despite methods used to account for impact;
Kuczmarski, 2016^34^ | 2111 | Adults, ~48 y[underlined: ;] Baltimore City, Maryland; [underlined: Data source:] HANDLS | PIR: ≥ 125% poverty threshold vs. <125% poverty threshold | HEI-2010 | PIR ≥ 125% vs. <125%: 0.70 (0.49), NS | Did not account for confounders of: Food security; Some concerns with departure from intended exposure
Martin, 2015^40^ | 4799 | Children, 5 to 17 y of Mexican-origin; National dataset; [underlined: Data source:] NHANES, 1999-2010 | PIR-squared | HEI-2010 | −1.30, p<0.05 | Did not account for confounders of: Urban vs. Rural; Food security; Some concerns with missing data. Limited generalizability due to sample being only Mexican-origin children.
Nowlin, 2016^43^ | 11668 | Adults, ≥20 y not pregnant; National dataset; [underlined: Data source:] NHANES, 2007-2012 | PIR | HEI-2010 | Regression coefficient [SE]; PIR: ≥3.5 (ref) v. 1.3-3.49; ≥3.5 (ref) v. ≤1.29; No T2D, n=9,509: −2.47 [0.6], p<0.01; −3.15 [0.6], p<0.01; Undiagnosed T2D, n=451: 4.68 [2.1] NS; −1.47 [2.0] NS;; Diagnosed T2D, n=1708: 1.00 [1.4] NS; −0.96 [1.4] NS | Did not account for confounders of: Urban vs. Rural; Food security; Serious concerns with departure from intended exposures and reported results.
Orr, 2019^44^ | 5882 | Adults, ≥ 20 y with type 1 or 2 diabetes; National dataset; [underlined: Data source:] NHANES, 1999-2014 | PIR, based on % HH income at; 100%, 100–200%, >200% poverty threshold | HEI-2010 | PIR, <100% (ref):; 100-200% 0.74 95% CI: −0.79, 2.27, NS; >200% 3.65 95% CI: 2.35, 4.95, p<0.001; Δ HEI/y: 0.18 95% CI: 0.04, 0.33, p=0.01; Interaction, food security × NHANES cycle: NS | Did not account for confounders of: Urban vs. Rural; Some concerns with selection into study
Patetta, 2019^45^ | 8012 | Adults, 18 to 39 y; National dataset; [underlined: Data source:] NHANES 2011-14 | <180% poverty threshold (low), 180-350% poverty threshold (middle), >350% poverty threshold (high) | HEI-2015 | Low v. high income and mean HEI: 52.4 v.61.2, p<0.05; low v. middle: 52.4 v. 55.8, NS; middle v. high: 55.8 v. 61.2, NS | Did not account for confounders of: Urban vs. Rural; Cultural/racial diversity or disparities; Sex; Age; Food security
Shan, 2019^48^ | 43996 | Adults, ≥20 y; National dataset; [underlined: Data source:] NHANES, 1999-2016 | PIR: < 1, 1.3-3.49, ≥3.5 | HEI-2015 | PIR < 1.3:; 2009-10 55.6, 95% CI: 55.0, 56.1;; 2011-12 56 95% CI: 55.0, 56.9;; 2013-14 55.7 95% CI: 55.0, 56.4;; 2015-16 56.2 95% CI: 55.3, 57.2;; 2015-16 v. 1999-00 difference, 0.81, 95%; CI: −0.63, 2.26; NS; PIR 1.3-3.49:; 2009-10 57.1, 95% CI: 56.4, 57.8;; 2011-12 57.7, 95% CI: 57.0, 58.4;; 2013-14 57.2, 95% CI: 56.6, 57.8;; 2015-16 56.4, 95% CI: 55.6, 57.1;; 2015-16 v. 1999-00 difference: 1.32, 95% CI: 0.18, 2.46 p<0.001; PIR ≥3.5:; 2009-10 58.8, 95% CI: 58.1, 59.5;; 2011-12 59.9, 95% CI: 58.9, 60.8;; 2013-14 59.5, 95% CI: 58.8, 60.2;; 2015-16 59.3, 95% CI: 58.3, 60.3;; 2015-16 v. 1999-00 difference, 3.23, 95% CI: 1.71, 4.75, p< 0.001 | N/A
Taverno Ross, 2020^4^ *PCS | 260 | Children, 10 to 17 y; South Carolina; [underlined: Data source:] Transitions and Activity Changes in Kids study | Poverty based on the percentage of residents living in poverty in the census tract for the child’s home address. | HEI-2015 | HEI growth curve: 0.2 [0.1], p<0.05 | Did not account for confounders of: Urban vs. Rural; Food security
Thomson, 2019^52^ | 9000 | Children, 2 to 18 y[underlined: ;] National dataset; [underlined: Data source:] NHANES 2009-2014 | PIR: <1, ≥1 | HEI-2015 | Overall: PIR<1 vs. PIR ≥1, 53.9, 95% CI: 52.5, 55.4 vs.. 55.1, 95% CI: 54.1, 56.1, NS; By Race/Ethnicity (in figure): no significant differences in HEI by PIR in non-Hispanic black, Mexican American, other Hispanic or other race groups; Significant difference in non-Hispanic white group by PIR; By Age Group and by gender: No significant differences in HEI by PIR | Did not account for confounders of: Urban vs. Rural; Cultural/racial diversity or disparities; Sex; Age; Food security; Serious concerns with departure from intended exposures
Thomson, 2020^53^ | 8894 | Children, 2 to 18 y; National dataset; [underlined: Data source:] NHANES, 2009-2014 | PIR: <1, ≥1 | HEI-2015 | PIR< 1 v. PIR≥1, mean, 95% CI; Underweight: 47.7, 95% CI: 42.8, 52.8 v. 51.1, 95% CI: 46.6, 55.8, NS; Normal weight: 53.9, 95% CI: 52.2, 55.6 v.55.6, 95% CI: 54.5, 56.6, NS; Overweight: 55.2, 95% CI: 52.5, 57.9 v.54.4, 95% CI: 52.0, 56.7, NS; Obese: 53.3, 95% CI: 51.1, 55.5 v. 54.3, 95% CI: 51.2, 57.6, NS | Did not account for confounders of: Urban vs. Rural; Cultural/racial diversity or disparities; Sex; Age; Food security; Serious concerns due to missing data
Wilson, 2018^61^ | 3555 | Adults, ≥19 y, all Hispanic; National dataset; [underlined: Data source:] NHANES, 2007/08; 2009/10 Consumer Behavior Phone Follow-Up Modules | PIR ≤ 130% v. >130% poverty threshold | HEI-2010 | HEI <51.6: 1.18, 95% CI: 0.99,1.44; NS | Did not account for confounders of: Urban vs. Rural; Food security; Serious concerns due to missing data
Both income and Federal assistance program participation/eligibility
Gu, 2017^24^ | All y: 38,487 Y in or after 2008: 16,802 | Children, 2 to 18 y; National dataset; [underlined: Data source:] NHANES, 1999-2012 | Income: PIR NSLP/SBP; SBP; SNAP; | HEI-2010 | PIR ≤1.3 v. 1.31-3.5 v. >3.5:; 2007-2008, n=5,402: 47.8, 95% CI: 46.2, 49.4 v. 44.9, 95% CI: 43.3, 46.4 v. 46.8, 95% CI: 44.7, 48.8, p<0.001; 2009-2010, n=5,751: 48.0, 95% CI: 46.8, 49.2 v. 48.1, 95% CI: 46.2, 49.9 v. 48.2, 95% CI: 46.1, 50.2, NS; 2011-2012, n=5,649: 50.0, 95% CI: 48.6, 51.4 v. 49.7, 95% CI: 48.3, 51.2 v. 51.5, 95% CI: 49.3, 53.7, p=0.02; SNAP Yes v. No, Mean (95% CI); 2007-2008: 47.0 (45.2, 48.8) v. 49.0 (46.5, 51.5), p=0.007; 2009-2010: 48.2 (46.7, 49.7) v. 48.0 (45.9, 50.1), NS; 2011-2012: 49.6 (47.9, 51.2) v. 51.1 (49.0, 53.3), p=0.004; All years combined: NS; WIC Yes v. No, Mean (95% CI); 2007-2008: 51.2 (49.1, 53.3) v. 53.4 (51.3, 55.6), NS; 2009-2010: 53.7 (51.2, 56.1) v. 51.2 (47.9, 54.5), NS; 2011-2012: 55.8 (53.9, 57.8) v. 51.3 (48.9, 53.7), p=0.008; All years combined: Higher v. Lower (numbers not reported), p=0.006; NSLP/SBP Yes v. No, Mean (95% CI); 2007-2008: 45.2 (44.2, 46.2) v. 47.5 (43.8, 51.3), p<0.001; 2009-2010: 46.8 (45.6, 48.1) v. 43.2 (40.2, 46.2), NS; 2011-2012: 49.0 (47.8, 50.3) v. 46.8 (43.2, 50.4), NS; All years combined: Lower v. Higher (numbers not reported). p=0.003 | Did not account for confounders of: Urban vs. Rural; Food security; Some concerns with departure from intended exposure
Gupta, 2020^25^ | 450 | Adults, ~ 51.1y, primary food shoppers with low access to healthy food retail; Ohio; [underlined: Data source:] N/A | SNAP participation in past 12 mo; WIC participation in past 12 mo; Other federal assistance in past 12 mo (TANF, Medicaid, disability, or SSI) Income: <$10K, $10,001-$20K, $20,001-$30K, $30,001-$40K, >$40,001 (ref). | HEI-2010 | Income, >$40,001 (ref): <$10K β=−2.3, NS; $10,001-$20K β=−2.9, NS; $20,001-$30K β=−0.7; $30,001-$40K β=−1.8, NS;; SNAP, non-participation (ref): β=−2.5, p=0.04;; WIC, non-participation (ref): β=−2.2, NS; Other: β=0.4, NS; | Some concerns with departure from intended exposure; Serious concerns with selection of reported results; Limited generalizability to those with higher access to healthy food retail.
Hanson, 2013^26^ | 2376 | Children, 6 to 17 y; National dataset; [underlined: Data source:] NHANES, 2003-2008 | Family Income: <200% poverty threshold (ref), >200% poverty threshold;; NSLP: no meals (ref), school lunch only, school breakfast and lunch; | HEI-2005 | [underlined: Income, >200% v. <200% poverty threshold:]; weekday, 51.2 95% CI: 49.0, 51.4 v. 50.2 95% CI: 49.0, 51.4, NS;; weekend, 47.6 95% CI: 46.1, 49.2 v. 48.9 95% CI: 47.8, 50.0, NS;; difference, +3.3 95% CI: 1.7, 5.0 v. +1.3 95% CI: 0.2, 2.5, NS; [underlined: NSLP participation, NSLP only v. no meals, NSLP+SBP v. no meals:]; weekday: 50.0 95% CI: 48.7, 51.2 v. 52.1 95% CI: 50.3, 53.9, p<0.05, 50.5 95% CI: 49.4, 51.8 v. 52.1 95% CI: 50.3, 53.9, NS, weekend, 48.5 95% CI: 46.8, 50.2 v. 46.9 95% CI: 45.0, 48.9, NS, 48.5 95% CI: 47.4, 49.7 v. 46.9 95% CI: 45.0, 48.9, NS; difference, +1.4 95% CI: −0.3, 3.2 v. +5.2 95% CI: 2.8, 7.6, p<0.05, +1.9 95% CI: 0.7, 3.1 v. +5.2 95% CI: 2.8, 7.6, p<0.05; | Serious concerns due to not accounting for confounders of: Urban vs. Rural; Cultural/racial diversity or disparities; Sex; Age; Food security; Serious concerns with classification of exposure, departure from intended exposure, missing data, and selection of reported results related to intent of study to capture weekday/weekend changes in HEI.
Hill, 2020^28^ | 168 | Adult, ≥18 y, pregnant women in 2nd trimester recruited from WIC clinic[underlined: ;] North Carolina; [underlined: Data source:] N/A | Monthly income: $0-1,000, ≥ $1,001; SNAP: Receives benefits or not | HEI-2010 | Monthly income: $0-$1000, 54.96 (14.16) 95%CI: 52.19, 57.72, v. ≥ $1001, 57.36 (13.11) 95%CI: 54.68, 60.05; NS; SNAP: receives benefits, 56.61 (13.36) 95%CI: 54.05,59.17 v. not receiving benefits, 55.51 (14.05) 95%CI: 52.63, 58.48; NS | Did not account for confounders of: Urban vs. Rural; Cultural/racial diversity or disparities; Age; Food security; Some concerns with selection into study, classification of exposure, departure from intended exposures, missing data, and reported results. Limited generalizability to those who are not pregnant and without WIC
Kane, 2018^31^ | 242 | Adults, >18 y, diagnosed with cancer currently receiving treatment; Ohio; [underlined: Data source:] N/A | Income/mo: ≥$4K, $3K-$3999, $2K-$2999, $1K-$1999, <$1K; Federal Food Assistance: SNAP, other, none | HEI-2010 | Bivariate-Income/mo, ≥$4K 64.69 (10.52) (ref): $3K-$3999 63.61 (12.66), $2K-$2999 60.63 (11.01), $1K-$1999 57.25 (11.55), <$1K 56.44 (12.12), p.0.001; Bivariate-Fed Food Assistance: None 62.55 (11.61) (ref): SNAP 55.18 (9.59), Other 55.73 (16.39), p≤0.01; Regression - Income/mo, ≥$4K (ref): $3K-$3999/mo, β=0.79, 95% CI: −2.97, 4.55, p=0.68 | Did not account for confounders of: Urban vs. Rural; Cultural/racial diversity or disparities; Food security; Serious or some concerns with selection into study, classification of exposures, departure from intended exposures, missing data, and reported results.
Kay, 2020^32^ | 231 | Children, 24 to 34 mo non-HM fed; North Carolina, Florida, California, New York; [underlined: Data source:] Greenlight Intervention Study, a cluster RCT | Low income < $19,999; Higher income ≥ $20K; WIC participation v. not | HEI-2010 | Low income, 62.9 (10.3) v. Higher income, 62.8 (10.7); NS; WIC benefits, 62.8 (10.5) v. not, 63.4 (10.4); NS | Did not account for confounders of: Urban vs. Rural; Some concerns with selection into study, missing data, and outcome measurement. Limited generalizability
Kinderknecht, 2020^33^ | 6389 | Children, 5 to 18 y, participating in NSL; National dataset; [underlined: Data source:] NHANES, 2007-2016 | NSLP participation or not, before and after Healthy, Hunger-Free Kids Act (HHFKA); Income: ≤130% poverty threshold (low); >130%-≤185% poverty threshold (low-middle); and >185% poverty threshold (middle-high) | HEI-2010 | Stratified by income, difference between before and after HHFKA for NSLP participants v. nonparticipants:; low income, 3.4 95% CI: 0.5,6.3, p=0.02; low-middle income, 4.7 95% CI: 0.8,8.7, p=0.02;; middle-high income, 1.9 95% CI: −0.08,4.5; NS | Did not account for confounders of: Urban vs. Rural; Food security; Serious or some concerns with selection into study, classification of exposures, departure from intended exposures, missing data, and reported results. Limited generalizability
Liu, 2020^39^ | 31420 | Children, 2 to 19 y[underlined: ;] National dataset; [underlined: Data source:] NHANES 1999-2016 | PIR: <1.30, 1.30-1.849, 1.85-2.99, ≥3.00; SNAP: Yes/No; WIC: Yes/No; NSLP/SBP: Yes/No | HEI-2015 | [underlined: 2007-08] PIR: <1.30, 1.30-1.849, 1.85-2.99, ≥3.00]: 48.1 (46.4, 49.7), 46.0 (44.6, 47.4), 47.0 (45.3, 48.8), 49.1 (47.7, 50.5);; SNAP Yes: 47.0 (45.4, 48.6), No: 48.5 (47.3, 49.7); WIC Yes: 49.7 (48.4, 51.0), No: 47.9 (46.7, 49.1); NSLP/SBP Yes: 46.4 (45.1, 47.6), No: 48.9 (47.6, 50.2); [underlined: 2009-10] PIR: <1.30, 1.30-1.849, 1.85-2.99, ≥3.00]: 48.6 (47.4, 49.8), 50.0 (47.6, 52.5), 49.4 (47.2, 51.7), 50.0 (48.9, 51.1); SNAP Yes: 49.2 (48.1, 50.2), No: 49.7 (48.5, 50.8); WIC Yes: 51.5 (49.9, 53.0), No: 49.2 (48.2, 50.2); NSLP/SBP Yes: 48.2 (47.3, 49.0), No: 50.2 (49.1, 51.4); [underlined: 2011-12:] PIR: <1.30, 1.30-1.849, 1.85-2.99, ≥3.00: 50.0 (48.9, 51.1), 51.2 (49.7, 52.7), 50.1 (48.5, 51.8), 53.4 (51.6, 55.2); SNAP Yes: 49.6 (48.7, 50.5), No: 52.0 (51.2, 52.8); WIC Yes: 52.8 (51.2, 54.5), No: 51.0 (50.1, 51.8); NSLP/SBP Yes: 49.2 (48.3, 50.1), No: 52.3 (51.4, 53.3); [underlined: 2013-14:] PIR: <1.30, 1.30-1.849, 1.85-2.99, ≥3.00: 49.6 (48.2, 51.1), 49.9 (48.2, 51.7), 49.3 (47.6, 50.9), 50.7 (48.7, 52.8); SNAP Yes: 50.1 (48.9, 51.2), No: 49.9 (48.8, 51.1); WIC Yes: 51.3 (49.3, 53.2), No: 49.7 (48.8, 50.6); NSLP/SBP Yes: 49.2 (48.0, 50.3), No: 50.4 (49.2-51.5); [underlined: 2015-16 (no SNAP or WIC data this cycle)]:; PIR: <1.30, 1.30-1.849, 1.85-2.99, ≥3.00: 48.3 (46.7, 49.9), 48.8 (47.2, 50.4), 50.7 (48.8, 52.7), 50.1 (48.3, 51.9);; NSLP/SBP Yes: 47.9 (46.6, 49.2), No: 50.8 (49.5, 52.1) | Serious risk due to confounding due to not accounting for confounders of: Urban vs. Rural; Cultural/racial diversity or disparities; Sex; Age; Food security
Tovar, 2020^55^ | 119 | Child-care centers with providers and 374 children; Providence, Rhode Island; [underlined: Data source:] Healthy Start/Comienzos Sanos | Income: <$25k, $25,001-$50k, $75k+; Federal: Receives CACFP subsidies (Yes/No) | HEI-2015 | Income: <$25k (ref); $25,001-$50k, β=2.9 [3.0], p=0.3; $75k+, β=−5.6 [4.0] p=0.17, NS; CACFP: No (ref); Yes; β=4.6 [2.6], p=0.08, NS | Did not account for confounders of: Urban vs. Rural; Age; Food security; Serious/some concerns on most domains of bias
Weinfield, 2021^59^ | 1223 | Dyads of Mothers with child ~ 3 y[underlined: ;] National dataset; [underlined: Data source:] Special Supplemental Nutrition Program for WIC Infant and Toddler Feeding Practices Study-2 | Poverty: >130% poverty threshold, 75% or less, >75% and <130% poverty threshold; WIC Duration: Low, Intermediate, High | HEI-2015 | Adjusted model WIC duration: Low (ref); Intermediate, β=0.36, 95% CI: 0.04, 0.69, p=0.03; High, β=0.41, 95% CI: 0.12, 0.71, p=0.007; Unadjusted model Poverty threshold: >130% (ref); 75% or below, β=0.86, 95%CI: −0.64, 2.35, NS; 75%+ and <130%, β=0.16, 95% CI: −0.88, 1.20, NS | Did not account for confounders of: Urban vs. Rural; Food security; Serious concerns with departure from intended exposures; Indirectly compared exposure via WIC duration
Federal participation/ eligibility
Allen, 2016^6^ | 1741 | Adults, 30 to 64 y; Baltimore, Maryland; [underlined: Data source:] HANDLS | SNAP participation v. not | HEI-2010 | SNAP: −2.74 [0.90], p=0.002; Food insecurity * SNAP: −0.80 [0.39], p=0.042; Covariate of PIR was significant predictor of HEI: −1.14 [0.57], p=0.044 | Some concerns with selection bias due to missing f/u; Methods used to assess exposure not well defined; Some concerns with departure from intended exposure due to SNAP status instability
Condon, 2015a^13^ | 16689 | Children and Adults, ≥2 y; National dataset; [underlined: Data source:] NHANES, 2007-2010; MPED 2.0; CNPP Fact Sheet No. 1, 2006 | SNAP: eligibility and participation | HEI-2005 | SNAP (ref) v. income eligible nonparticipants v. higher income nonparticipants:; All ages: 56.8 v. 60.3, p<0.05 v. 60.2, p<0.05;; Children: 57.9 v. 61.0, p<0.05 v. 59.0, NS;; Adults: 53.9 v. 58.2, p<0.05 v. 59.0, p<0.05;; Older adults: 64.0 v. 65.6, NS v. 65.6, NS;; ≥16 y, matched SNAP-eligible participants, n=975 v. nonparticipants, n=572: 54.1 v. 55.8, NS | Did not account for confounders of: Urban vs. Rural; Some concerns with selection into study, departure from intended exposure, and missing data
Nguyen, 2014^41^ | 4211 | Adults, 20 to 64 y; National dataset; [underlined: Data source:] NHANES, 2003-2010 | SNAP participation v. income eligible non-participants determined by PIR or ≤ 130% poverty threshold | HEI-2010 | SNAP participants 42.58 [0.33] v. eligible, nonparticipants 44.36 [0.27], p.0.001. Sensitivity analyses revealed effects by sex, ethnicity, and security status. | Did not account for confounders of: Cultural/racial diversity or disparities; Sex; Age; Food security; Exposure/comparator was not directly related to question of interest
Nguyen, 2015^42^ | 8333 | Adults, ~46 y, all low-income; National dataset; [underlined: Data source:] NHANES, 2003-2010 | SNAP participation | HEI-2010 | Overall: β= −3.18 [0.53] p<0.01; SNAP + marginal food security: β=3.46 [0.99] p<0.01; SNAP + low food security: β=1.98 [0.88], p<0.05; SNAP + very low food security: β=3.84 [1.04] p<0.01 | Did not account for confounders of: Urban vs. Rural; Some concerns with selection into study, classification of exposures, and departure from intended exposure. Limited generalizability
Singleton, 2020^49^ | 14331 | Adults, ≥18 y; National dataset; [underlined: Data source:] NHANES, 2009-2014 | SNAP participation, eligible non-participants, ineligible non-participants via PIR | HEI-2015 | SNAP Participants: PIR: β=0.24 [0.26], NS;; Eligible Nonparticipants: PIR: β=−0.34 [1.17], NS;; Ineligible Nonparticipants: PIR: β=0.58 [0.17] | Did not account for confounders of: Urban vs. Rural; Serious concerns with departure from intended exposures
Todd, 2015^54^ | 1480 | Adults, ~ 41y, all SNAP participants; National dataset; [underlined: Data source:] NHANES, 2007-2010 | SNAP participation (days since received) | HEI-2010 | β= −0.090 [0.033], p<0.05 | Did not account for confounders of: Urban vs. Rural; Cultural/racial diversity or disparities; Sex; Age; Limited generalizability
Bremer, 2018^2^ | 146 | Adults, > 18 y, from the intervention group of the trial; southwestern Virginia; [underlined: Data source:] SIPsmartER trial | SNAP-participants, SNAP-eligible nonparticipants, and Ineligible-nonparticipants | HEI-2010 | At baseline, SNAP participants v. Eligible, nonparticipants v. Ineligible: 39.2 (10.8) v. 42.1 (13.6) v. 45.7 (12.5), p=0.160; NS; After 6 mo, SNAP participants v. Eligible, nonparticipants v. Ineligible: 41.3 (10.7) v. 42.2 (11.3) v. 50.8 (14.0), p=0.160; NS | Did not account for confounders of: Urban vs. Rural; Food security; Some concerns with classification of exposure due to self-selection/proxy calculations; Some concerns with departure from intended exposure due to lack of accounting for food insecurity/hunger;
Condon, 2015b^14^ | 5814 | Children in school, 5 to 18 y; National dataset; [underlined: Data source:] NHANES, 2005-2010 | NSLP participants v. nonparticipants (all income eligible for free/RP meals); NSLP participants v. nonparticipants (all higher income) | HEI-2005 | NSLP participants v. nonparticipants (all free/RP meals): 60.5 [1.24] v. 55.1 [1.23], p<0.05; In 5-8 y, NS; In 9-13 y, 61.3 [1.75] v. 54.2 [1.78], p<0.01 (similar results by sex in boys and girls); In 14-18 y, NS; NSLP participants v. nonparticipants (all higher income): 56.8 [1.19] v. 57.1 [1.31], NS; In 5-8 y, NS; In 9-13 y, NS; In 14-18 y, NS | Did not account for confounders of: Urban/rural, Cultural/racial diversity or disparities; Food security; Some concerns with selection into study (excluded children who bring lunch from home), departure from intended exposure, and missing data.
Fox, 2019^19^ | 4141 | Children in Elementary, Middle, and High school; National dataset; [underlined: Data source:] School Nutrition and Meal Cost Study | NSLP participation v. not; SBP participation v. not | HEI-2010 | NSLP vs.. nonparticipants:; Elementary-school: 65.1 v. 60.8, NS; Middle-school: 65.9 v. 62.9, NS; High-school: 63.6 v. 59.7, NS; All students: 65.2 v. 60.6, p<0.05; SBP vs.. nonparticipants:; Elementary-school: 66.4 v. 63.4, NS; Middle-school: 63.7 v. 64.9, NS; High-school: 63.8 v. 59.8, p<0.05; All students: 65.5 v. 62.8, NS | Did not account for confounders of: Food security
Gearan, 2020^21^ | 2165 | Children, 6 to 19 y; National dataset; [underlined: Data source:] School Nutrition and Meal Cost Study | NSLP participation or not on day of 24 hour recall (9% missing data imputed) | HEI-2010 | NSLP v. nonparticipants: 65% v. 61%, p<0.05; 24h intake, both lower-income: 65.3 v. 61.4; difference: 3.9; NS; 24h intake, both higher-income: 65 v. 60.9, difference: 4, p<0.05; Lunch intakes, both lower-income: 79.8 v. 68.0, difference: 11.8, p<0.05; Lunch intakes, both higher-income: 80.5 v. 62.1,difference: 18.4, p<0.05 | Did not account for confounders of: Urban vs. Rural; Food security; Some concerns related to missing data
Gregory, 2013^23^ | 5105 | Households of all low-income participants ≤ 200% poverty threshold; National dataset; [underlined: Data source:] NHANES, 2003-2008; ERS | SNAP participation v. nonparticipation over 12 mo | HEI-2005 | SNAP: 51.02 v. Non-SNAP 47.49, p<0.01; SNAP v. Non-SNAP: OLS marginal effects −0.66 [0.65], NS; SNAP v. Non-SNAP: MFX Tx effects MLE −1.56 [0.25], p<0.01 | Did not account for confounders of: Urban vs. Rural; Food security; Some concerns with classification of exposure and departure from intended exposure; Limited generalizability
Hearst, 2016^27^ | 739 | Children/Adolescents, 9th to 10th grade; rural Minnesota; [underlined: Data source:] Fueling Academics and Strengthening Teens Study (Break-FAST) | NSLP status: free/reduced price lunch v. full-price lunch | HEI-2010 | Free/Red. cost lunch v. Full-price lunch: β= −0.60 [0.79], p=0.45, NS; Full-price lunch, n=472: 51.8 v. Free/Red. cost lunch, n=267: 52.1, NS | Did not account for confounders of: Food security; Some concerns with selection into study, departure from intended exposures, and missing data.
Hudak, 2021^29^ | 2797 | Children, 2 to 18 y[underlined: ;] National dataset; [underlined: Data source:] NHANES, 2007-2008; 2011-2012 | SNAP-eligible <150% poverty threshold; Nearly SNAP-eligible between 150% and 250% poverty threshold | HEI-2010 | pre-ARRA: SNAP-eligible, 46.4 [1.02] v. nearly eligible 43.7 [1.00]; NS; post-ARRA: SNAP-eligible, 47.3 [0.73] v. nearly eligible 46.6 [0.73]; NS; SNAP benefit increase, overall before v. after ARRA: −1.99; ARRA-increase by age: Toddlers 2-3y, n=665: 2.55 [3.47]; Preschoolers 4-5y, n=550: −2.61 [3.01]; Children 6-11 y, n=1186: −2.86 [2.48]; Adolescents 12-18y, n=1186: −4.61 (2.21), p<0.05 | Did not account for confounders of: Urban vs. Rural; Some concerns with selection into study and classification of exposures; Serious concerns due to departure from intended exposures.
Landry, 2019^35^ | 598 | Children, 3rd to 5th grade; Austin, Texas; [underlined: Data source:] TX Sprouts | SNAP Participation: Yes/No | HEI-2015 | Unadjusted: SNAP Participation: Yes (ref); No, β=1.6, SE: 1.25, 95% CI: −0.85, 4.05, p=0.200, NS | Did not account for confounders of: Urban vs. Rural; Some concerns with departure from intended exposures, missing data, outcome measurement, and reported results.
Leung, 2012^37^ | 3835 | Adults, non-elderly[underlined: ;] National dataset; [underlined: Data source:] NHANES 1999-2008 | SNAP Participants vs. non-participants | HEI-2005 | HEI: SNAP Nonparticipants (ref), SNAP Participants, RD=0.98, 95% CI: 0.94, 1.02, NS | Accounted for confounders; Some concerns with departure from intended exposures (i.e. variation in SNAP status), missing data, and reported results.
Leung, 2013^38^ | 5193 | Children, 4 to 19 y, all low-income ≤ 130% poverty threshold[underlined: ;] National dataset; [underlined: Data source:] NHANES, 1999-2008 | SNAP participants v. income eligible non-participants (former participants within last 12 mo were excluded) | HEI-2005 | SNAP Nonparticipants, 47.2 (0.5) v. participants, 45.6 (0.6), NS | Did not account for confounders of: Urban vs. Rural; Some concerns with departure from intended exposures, missing data, and reported results.
Sanjeevi, 2021^47^ | Adult: 2784; Child: 2553 | Adults and Children, 3 to 75 y, all low-income[underlined: ;] National dataset; [underlined: Data source:] NHANES 2011-2016 | SNAP current v. former participants with benefits cut off in past year; cut off for >1 y | HEI-2015 | Adults: Current SNAP (ref); Benefits cut off in past year: β=0.02 [1.25], p=0.99, NS; Benefits cut off >1 y: β=−0.66 [0.94], p=0.49, NS; Children: Current SNAP (ref); Benefits cut off in past year: β=−0.03 [1.58], p=0.99, NS; Benefits cut off >1 y: β= −1.34 [0.99], p=0.18, NS | Did not account for confounders of: Urban vs. Rural; Serious concerns with departure from intended exposures; Limited generalizability
Thomas Berube, 2019^51^ | 519 | Adults, all Hispanic women who are pregnant; New York City, New York; [underlined: Data source:] Starting Early Trial | WIC Participation (yes/no); SNAP Participation (yes/no) | HEI-2015 | WIC Participation: No (ref), Yes, β=2.1, 95% CI: −0.1, 4.4, p=0.06, NS; SNAP: No (ref), Yes, β=−0.3, 95% CI: −1.9, 1.3, p=0.73, NS | Did not account for confounders of: Urban vs. Rural; Cultural/racial diversity or disparities; Food security; Limited generalizability
Waehrer, 2015^56^ | 4158 | Adults, ≥ 19 y; National dataset; [underlined: Data source:] NHANES, 2007-2010 | SNAP eligible (≤ 150% poverty threshold) v. ineligible (150-250% poverty threshold) | HEI-2005 | pre-ARRA ≤ 150%: 53.9; post-ARRA ≤ 150%: 53.5, NS; pre-ARRA 150-250%: 54.9; post-ARRA 150-250%: 56.6, NS | Did not account for confounders of: Urban vs. Rural; Food security; Exposure was not directly related to the question of interest
Wang, 2021^57^ | 157 | Adults, all older adults/adults with disabilities receiving Supplemental Security Income (SSI); California; [underlined: Data source:] N/A | SNAP eligibility and participation | HEI-2015 | Mean HEI-2015 score SNAP non-recipient, n=43: 45.8 v. recipient, n=114: 45.0, NS; Expansion: baseline, n=213: 44.3 v. follow-up, n=157: 43.6, NS | Did not account for confounders of: Urban vs. Rural; Food security; Serious concerns due to missing data; Exposure was not directly related to the question of interest

a Abbreviations: ARRA, American Recovery and Reinvestment Act of 2008; EFNEP, Expanded Food and Nutrition Education Program; FPG, Federal Poverty Guidelines; HANDLS, Healthy Aging in Neighborhoods of Diversity across the Life Span Study; HEI, healthy eating index; Healthy, Hunger-Free Kids Act (HHFKA); HH, household; mo, months; N/A, not applicable or available; NHANES, National Health and Nutrition Examination Survey; NSLP, National School Lunch Program; NS, not statistically significant; % percent; PIR: poverty-to-income ratio; SBP, School Breakfast Program; SNAP, Supplemental Nutrition Assistance Program; SSI, Supplemental Security Income; WIC, Supplemental Assistance Program for Women, Infants and Children; y, years

Table 2-c Risk of bias for observational studies examining income and HEI^a^

Article | Confounding | Selection of participants | Classification of exposures | Deviations from intended exposures | Missing data | Outcome measurement | Selection of the reported result
Beydoun, 2018^1^ *PCS | SERIOUS | LOW | MODERATE | SERIOUS | MODERATE | MODERATE | SERIOUS
Bremer, 2018^2^ *PCS | SERIOUS | MODERATE | MODERATE | SERIOUS | MODERATE | MODERATE | LOW
Covington, 2020^3^ *PCS | SERIOUS | MODERATE | LOW | LOW | MODERATE | LOW | MODERATE
Taverno Ross, 2020^4^ *PCS | SERIOUS | MODERATE | MODERATE | LOW | MODERATE | MODERATE | MODERATE
Aggarwal, 2016^5^ | SERIOUS | MODERATE | LOW | MODERATE | MODERATE | LOW | MODERATE
Allen, 2016^6^ | SERIOUS | SERIOUS | MODERATE | SERIOUS | MODERATE | LOW | LOW
Beatty, 2014^7^ | SERIOUS | MODERATE | MODERATE | MODERATE | LOW | SERIOUS | SERIOUS
Bekelman, 2021^8^ | SERIOUS | MODERATE | LOW | MODERATE | MODERATE | LOW | LOW
Beydoun, 2015^9^ | MODERATE | SERIOUS | LOW | MODERATE | MODERATE | LOW | MODERATE
Byker Shanks, 2020^10^ | MODERATE | MODERATE | LOW | LOW | LOW | LOW | MODERATE
Chen, 2018^11^ | MODERATE | MODERATE | LOW | LOW | LOW | MODERATE | LOW
Coltman, 2013^12^ | CRITICAL | SERIOUS | LOW | MODERATE | MODERATE | LOW | MODERATE
Condon, 2015a^13^ | MODERATE | MODERATE | LOW | MODERATE | SERIOUS | MODERATE | MODERATE
Condon, 2015b^14^ | SERIOUS | MODERATE | LOW | MODERATE | MODERATE | LOW | MODERATE
Deierlein, 2014^15^ | LOW | MODERATE | LOW | MODERATE | LOW | LOW | MODERATE
Deierlein, 2021^16^ | MODERATE | SERIOUS | LOW | SERIOUS | LOW | LOW | MODERATE
Drewnowski, 2016^17^ | LOW | MODERATE | MODERATE | MODERATE | LOW | LOW | MODERATE
Flórez, 2015^18^ | LOW | LOW | MODERATE | MODERATE | MODERATE | MODERATE | MODERATE
Fox, 2019^19^ | MODERATE | MODERATE | LOW | MODERATE | MODERATE | LOW | MODERATE
Freedman, 2019^20^ | LOW | MODERATE | MODERATE | MODERATE | LOW | LOW | MODERATE
Gearan, 2020^21^ | SERIOUS | MODERATE | LOW | LOW | MODERATE | LOW | LOW
Gibbs, 2016^22^ | SERIOUS | MODERATE | LOW | LOW | LOW | LOW | LOW
Gregory, 2013^23^ | SERIOUS | MODERATE | MODERATE | MODERATE | LOW | LOW | MODERATE
Gu, 2017^24^ | SERIOUS | MODERATE | LOW | SERIOUS | LOW | LOW | MODERATE
Gupta, 2020^25^ | LOW | MODERATE | LOW | MODERATE | LOW | LOW | SERIOUS
Hanson, 2013^26^ | SERIOUS | MODERATE | SERIOUS | SERIOUS | MODERATE | LOW | SERIOUS
Hearst, 2016^27^ | MODERATE | SERIOUS | LOW | MODERATE | MODERATE | LOW | MODERATE
Hill, 2020^28^ | SERIOUS | SERIOUS | MODERATE | MODERATE | MODERATE | LOW | MODERATE
Hudak, 2021^29^ | MODERATE | MODERATE | MODERATE | SERIOUS | MODERATE | LOW | LOW
Huffman, 2014^30^ | SERIOUS | MODERATE | LOW | MODERATE | MODERATE | LOW | MODERATE
Kane, 2018^31^ | SERIOUS | SERIOUS | MODERATE | MODERATE | MODERATE | LOW | SERIOUS
Kay, 2020^32^ | SERIOUS | MODERATE | LOW | LOW | MODERATE | MODERATE | LOW
Kinderknecht, 2020^33^ | SERIOUS | MODERATE | SERIOUS | MODERATE | SERIOUS | LOW | SERIOUS
Kuczmarski, 2016^34^ | MODERATE | MODERATE | LOW | MODERATE | LOW | LOW | LOW
Landry, 2019^35^ | MODERATE | MODERATE | LOW | MODERATE | MODERATE | MODERATE | MODERATE
Laster, 2013^36^ | SERIOUS | MODERATE | MODERATE | LOW | LOW | LOW | LOW
Leung, 2013^38^ | MODERATE | MODERATE | LOW | MODERATE | SERIOUS | LOW | MODERATE
Leung, 2012^37^ | LOW | MODERATE | LOW | MODERATE | MODERATE | LOW | MODERATE
Liu, 2020^39^ | SERIOUS | MODERATE | MODERATE | MODERATE | MODERATE | LOW | MODERATE
Martin, 2015^40^ | SERIOUS | MODERATE | LOW | LOW | MODERATE | LOW | LOW
Nguyen, 2014^41^ | MODERATE | MODERATE | MODERATE | MODERATE | LOW | LOW | LOW
Nyguen, 2015^42^ | MODERATE | MODERATE | LOW | MODERATE | MODERATE | LOW | MODERATE
Nowlin, 2016^43^ | SERIOUS | MODERATE | LOW | SERIOUS | MODERATE | LOW | SERIOUS
Orr, 2019^44^ | MODERATE | SERIOUS | LOW | MODERATE | MODERATE | LOW | MODERATE
Patetta, 2019^45^ | SERIOUS | MODERATE | LOW | MODERATE | MODERATE | LOW | MODERATE
Richards Adams, 2019^46^ | MODERATE | SERIOUS | LOW | MODERATE | LOW | LOW | MODERATE
Sanjeevi, 2021^47^ | MODERATE | MODERATE | LOW | SERIOUS | MODERATE | LOW | SERIOUS
Shan, 2019^48^ | SERIOUS | MODERATE | LOW | MODERATE | SERIOUS | LOW | LOW
Singleton, 2020^49^ | MODERATE | MODERATE | MODERATE | SERIOUS | MODERATE | LOW | MODERATE
Springfield, 2019^50^ | SERIOUS | SERIOUS | LOW | LOW | LOW | LOW | LOW
Thomas Berube, 2019^51^ | SERIOUS | MODERATE | LOW | MODERATE | MODERATE | LOW | MODERATE
Thomson, 2020^53^ | SERIOUS | MODERATE | LOW | MODERATE | SERIOUS | LOW | LOW
Thomson, 2019^52^ | SERIOUS | LOW | MODERATE | SERIOUS | MODERATE | LOW | LOW
Todd, 2015^54^ | SERIOUS | MODERATE | SERIOUS | MODERATE | MODERATE | LOW | MODERATE
Tovar, 2020^55^ | SERIOUS | MODERATE | MODERATE | MODERATE | No Information | LOW | SERIOUS
Waehrer, 2015^56^ | MODERATE | SERIOUS | LOW | MODERATE | LOW | LOW | LOW
Wang, 2021^57^ | SERIOUS | LOW | LOW | LOW | LOW | LOW | MODERATE
Weatherspoon, 2017^58^ | MODERATE | SERIOUS | MODERATE | SERIOUS | MODERATE | MODERATE | MODERATE
Weinfield, 2021^59^ | SERIOUS | MODERATE | LOW | SERIOUS | MODERATE | LOW | LOW
Wilcox, 2020^60^ | SERIOUS | MODERATE | LOW | SERIOUS | MODERATE | LOW | MODERATE

a Possible ratings of low, moderate, serious, critical, or no information determined using the “Risk of Bias for Nutrition Observational Studies” tool (RoB-NObs) ( Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.)

## References of the articles included in the income and HEI rapid review

1 Beydoun MA, Fanelli-Kuczmarski MT, Poti J, . Longitudinal change in the diet’s monetary value is associated with its change in quality and micronutrient adequacy among urban adults. PLoS One. 2018;13(10):e0204141. doi: 10.1371/journal.pone.0204141. eCollection 2018.30312298
2 Bremer MC, Zoellner JM, Misyak SA, Hedrick VE. Dietary intake changes in response to a sugar-sweetened beverage reduction trial for various supplemental nutrition assistance program (SNAP) eligibility groups. J Nutr Educ Behav. 2018;50(9):931–936. doi: 10.1016/j.jneb.2018.07.010.30297018
3 Covington L, Armstrong B, Trude ACB, Black MM. Longitudinal associations among diet quality, physical activity and sleep onset consistency with body mass index z-score among toddlers in low-income families. Ann Behav Med. 2020. doi: 10.1093/abm/kaaa100.
4 Taverno Ross SE, Militello G, Dowda M, Pate RR. Changes in diet quality in youth living in south carolina from fifth to 11th grade. J Nutr Educ Behav. 2020;52(10):928–934. doi: 10.1016/j.jneb.2020.03.001. Epub 2020 Apr 23.32334976
5 Aggarwal A, Rehm CD, Monsivais P, Drewnowski A. Importance of taste, nutrition, cost and convenience in relation to diet quality: Evidence of nutrition resilience among US adults using National Health and Nutrition Examination Survey (NHANES) 2007-2010. Prev Med. 2016;90:184–192. doi: 10.1016/j.ypmed.2016.06.030. Epub 2016 Jun 29.27374943
6 Allen AJ, Kuczmarski MF, Evans MK, Zonderman AB, Waldstein SR. Race differences in diet quality of urban food-insecure blacks and whites reveals resiliency in blacks. J Racial Ethn Health Disparities. 2016;3(4):706–712. doi: 10.1007/s40615-015-0189-5. Epub 2015 Dec 10.27294760
7 Beatty TKM, Lin B-H, Smith TA. Is diet quality improving? Distributional changes in the United States, 1989–2008. American Journal of Agricultural Economics. 2014;96(3):769–789. http://search.ebscohost.com/login.aspx?direct=true&db=buh&AN=95479693&site=ehost-live.
8 Bekelman TA, Sauder KA, Rockette-Wagner B, Glueck DH, Dabelea D. Sociodemographic predictors of adherence to national diet and physical activity guidelines at age 5 years: the healthy start study. Am J Health Promot. 2021;35(4):514–524. doi: 10.1177/0890117120968654. Epub 2020 Oct 29.33118362
9 Beydoun MA, Fanelli-Kuczmarski MT, Allen A, . Monetary value of diet Is associated with dietary quality and nutrient adequacy among urban adults, differentially by sex, race and poverty status. PLoS One. 2015;10(11):e0140905. doi: 10.1371/journal.pone.0140905. eCollection 2015.26536243
10 Byker Shanks C, Ahmed S, Dupuis V, . Dietary quality varies among adults on the Flathead Nation of the Confederated Salish and Kootenai tribes in Montana. J Community Health. 2020;45(2):388–399. doi: 10.1007/s10900-019-00753-3.31602533
11 Chen XW, Cisse-Egbuonye N, Spears EC, Mkuu R, McKyer ELJ. Children’s healthy eating habits and parents’ socio-demographic characteristics in rural Texas, USA. Health Educ J. 2018;77(4):444–457. 10.1177/0017896917752014.
12 Coltman AE, Keim KS, Chapman-Novakofski KM, Taylor CA. Assessing diet quality of a type 2 diabetes sample using the Healthy Eating Index 2005. Top Clin Nutr. 2013;28(2):145–153. 10.1097/TIN.0b013e31828d7a61.
13 Condon E, Drilea S, Jowers K, . Diet quality of americans by SNAP participation status: Data from the National Health and Nutrition Examination Survey, 2007-2010. Mathematica Policy Research;2015.
14 Condon E, Drilea S, Lichtenstein C, Mabli J, Madden E, Niland K. Diet quality of Americans by NSLP participation status: Data from the National Health and Nutrition Examination Survey, 2005-2010. Walter R. McDonald & Associates, Inc, and Mathematica Policy Research;2015.
15 Deierlein AL, Morland KB, Scanlin K, Wong S, Spark A. Diet quality of urban older adults age 60 to 99 years: the Cardiovascular Health of Seniors and Built Environment Study. J Acad Nutr Diet. 2014;114(2):279–287. doi: 10.1016/j.jand.2013.09.002. Epub 2013 Nov 18.24262516
16 Deierlein AL, Ghassabian A, Kahn LG, . Dietary quality and sociodemographic and health behavior characteristics among pregnant women participating in the New York university children’s health and environment study. Front Nutr. 2021;8:639425. doi: 10.3389/fnut.2021.639425. eCollection 2021.33898496
17 Drewnowski A, Aggarwal A, Cook A, Stewart O, Moudon AV. Geographic disparities in Healthy Eating Index scores (HEI-2005 and 2010) by residential property values: Findings from Seattle Obesity Study (SOS). Prev Med. 2016;83:46–55. doi: 10.1016/j.ypmed.2015.11.021. Epub 2015 Dec 3.26657348
18 Flórez KR, Dubowitz T, Ghosh-Dastidar MB, Beckman R, Collins RL. Associations between depressive symptomatology, diet, and body mass index among participants in the supplemental nutrition assistance program. J Acad Nutr Diet. 2015;115(7):1102–1108. doi: 10.1016/j.jand.2015.01.001. Epub 2015 Mar 10.25769748
19 Fox MK, Gearan E, Cabili C, . School nutrition and meal cost study final report volume 4: Student participation, satisfaction, plate waste, and dietary intakes. Mathematica Policy Research;2019.
20 Freedman DA, Bell BA, Clark JK, . Socioecological path analytic model of diet quality among residents in two urban food deserts. J Acad Nutr Diet. 2019;119(7):1150–1159. doi: 10.1016/j.jand.2019.02.012. Epub 2019 Apr 25.31031105
21 Gearan EC, Monzella K, Jennings L, Fox MK. Differences in diet quality between school lunch participants and nonparticipants in the United States by income and race. Nutrients. 2020;12(12). doi: 10.3390/nu12123891.
22 Gibbs HD, Kennett AR, Kerling EH, . Assessing the nutrition literacy of parents and its relationship with child diet quality. J Nutr Educ Behav. 2016;48(7):505–509.e501. doi: 10.1016/j.jneb.2016.04.006. Epub 2016 May 20.27216751
23 Gregory C, Ver Ploeg M, Andrews M, Coleman-Jensen A. Supplemental Nutrition Assistance Program (SNAP) participation leads to modest changes in diet quality. 2013:36.
24 Gu X, Tucker KL. Dietary quality of the US child and adolescent population: trends from 1999 to 2012 and associations with the use of federal nutrition assistance programs. Am J Clin Nutr. 2017;105(1):194–202. doi: 10.3945/ajcn.116.135095. Epub 2016 Nov 23.27881390
25 Gupta NR, Freedman DA. Food security moderates relationship between perceived food environment and diet quality among adults in communities with low access to healthy food retail. Pub Health Nutr. 2020:1–12. doi: 10.1017/S1368980020001317.
26 Hanson KL, Olson CM. School meals participation and weekday dietary quality were associated after controlling for weekend eating among U.S. school children aged 6 to 17 years. J Nutr. 2013;143(5):714–721. doi: 10.3945/jn.112.170548. Epub 2013 Mar 13.23486981
27 Hearst MO, Harnack LJ, Wang Q, Nanney MS. Dietary quality of diverse, rural adolescents using the Healthy Eating Index - 2010. Health Behav Policy Rev. 2016;3(6):519–527. doi: 10.14485/HBPR.3.6.1.30271808
28 Hill AM, Nunnery DL, Ammerman A, Dharod JM. Racial/ethnic differences in diet quality and eating habits among WIC pregnant women: Implications for policy and practice. Am J Health Promot. 2020;34(2):169–176. doi: 10.1177/0890117119883584. Epub 2019 Oct 28.31658816
29 Hudak KM, Racine EF, Schulkind L. An increase in SNAP benefits did not impact food security or diet quality in youth. J Acad Nutr Diet. 2021;121(3):507–519.e512. doi: 10.1016/j.jand.2020.09.030. Epub 2020 Nov 10.33187930
30 Huffman FG, Vaccaro JA, Zarini GG, Dixon Z. Comparison of two indices of diet quality with acculturation factors and demographics in Haitian Americans. Ecol Food Nutr. 2014;53(1):42–57. 10.1080/03670244.2013.774674.24437543
31 Kane K, Ilic S, Paden H, . An evaluation of factors predicting diet quality among cancer patients. Nutrients. 2018;10(8). doi: 10.3390/nu10081019.
32 Kay MC, Silver HJ, Yin HS, . Assessing diet quality in a racially and ethnically diverse cohort of low-income toddlers. J Pediatr Gastroenterol Nutr. 2020;71(5):679–685. doi: 10.1097/MPG.0000000000002871.33093378
33 Kinderknecht K, Harris C, Jones-Smith J. Association of the Healthy, Hunger-Free Kids Act with dietary quality among children in the US National School Lunch Program. Jama. 2020;324(4):359–368. doi: 10.1001/jama.2020.9517.32721008
34 Kuczmarski MF, Beydoun MA, Cotugna N, . Literacy contributes to greater higher diet quality in a socioeconomically diverse urban prospective cohort. Top Clin Nutr. 2016;31(1):47–58. 10.1097/TIN.0000000000000057.
35 Landry MJ, van den Berg AE, Asigbee FM, Vandyousefi S, Ghaddar R, Davis JN. Child-report of food insecurity is associated with diet quality in children. Nutrients. 2019;11(7). doi: 10.3390/nu11071574.
36 Laster LE, Lovelady CA, West DG, . Diet quality of overweight and obese mothers and their preschool children. J Acad Nutr Diet. 2013;113(11):1476–1483. doi: 10.1016/j.jand.2013.05.018. Epub 2013 Jul 16.23871105
37 Leung CW, Ding EL, Catalano PJ, Villamor E, Rimm EB, Willett WC. Dietary intake and dietary quality of low-income adults in the Supplemental Nutrition Assistance Program. Am J Clin Nutr. 2012;96(5):977–988. doi: 10.3945/ajcn.112.040014. Epub 2012 Oct 3.23034960
38 Leung CW, Blumenthal SJ, Hoffnagle EE, . Associations of food stamp participation with dietary quality and obesity in children. Pediatrics. 2013;131(3):463–472. doi: 10.1542/peds.2012-0889. Epub 2013 Feb 25.23439902
39 Liu J, Rehm CD, Onopa J, Mozaffarian D. Trends in diet quality among youth in the United States, 1999-2016. Jama. 2020;323(12):1161–1174. doi: 10.1001/jama.2020.0878.32207798
40 Martin MA, Van Hook JL, Quiros S. Is socioeconomic incorporation associated with a healthier diet? Dietary patterns among Mexican-origin children in the United States. Soc Sci Med. 2015;147:20–29. 10.1016/j.socscimed.2015.10.028.26523786
41 Nguyen BT, Shuval K, Njike VY, Katz DL. The Supplemental Nutrition Assistance Program and dietary quality among US adults: findings from a nationally representative survey. Mayo Clin Proc. 2014;89(9):1211–1219. doi: 10.1016/j.mayocp.2014.05.010. Epub 2014 Aug 5.25107469
42 Nguyen BT, Shuval K, Bertmann F, Yaroch AL. The Supplemental Nutrition Assistance Program, food insecurity, dietary quality, and obesity among U.S. adults. Am J Public Health. 2015;105(7):1453–1459. doi: 10.2105/AJPH.2015.302580. Epub 2015 May 14.25973830
43 Nowlin SY, Cleland CM, Vadiveloo M, D’Eramo Melkus G, Parekh N, Hagan H. Explaining racial/ethnic dietary patterns in relation to type 2 diabetes: an analysis of NHANES 2007-2012. Ethn Dis. 2016;26(4):529–536. doi: 10.18865/ed.26.4.529.27773980
44 Orr CJ, Keyserling TC, Ammerman AS, Berkowitz SA. Diet quality trends among adults with diabetes by socioeconomic status in the U.S.: 1999-2014. BMC Endocr Disord. 2019;19(1):54. doi: 10.1186/s12902-019-0382-3.31151439
45 Patetta MA, Pedraza LS, Popkin BM. Improvements in the nutritional quality of US young adults based on food sources and socioeconomic status between 1989-1991 and 2011-2014. Nutr J. 2019;18(1):32. doi: 10.1186/s12937-019-0460-4.31242913
46 Richards Adams IK, Figueroa W, Hatsu I, . An examination of demographic and psychosocial factors, barriers to healthy eating, and diet quality among African American adults. Nutrients. 2019;11(3). doi: 10.3390/nu11030519.
47 Sanjeevi N, Freeland-Graves JH, Sachdev PK. Association of loss of Supplemental Nutrition Assistance Program benefits with food insecurity and dietary intake of adults and children. Am J Clin Nutr. 2021. doi: 10.1093/ajcn/nqab082.
48 Shan Z, Rehm CD, Rogers G, . Trends in dietary carbohydrate, protein, and fat intake and diet quality among US adults, 1999-2016. Jama. 2019;322(12):1178–1187. doi: 10.1001/jama.2019.13771 31550032
49 Singleton CR, Young SK, Kessee N, Springfield SE, Sen BP. Examining disparities in diet quality between SNAP participants and non-participants using Oaxaca-Blinder decomposition analysis. Prev Med Rep. 2020;19:101134. doi: 10.1016/j.pmedr.2020.101134. eCollection 2020 Sep.32528823
50 Springfield S, Odoms-Young A, Tussing-Humphreys LM, Freels S, Stolley MR. A step toward understanding diet quality in urban african-american breast cancer survivors: a cross-sectional analysis of baseline data from the moving forward study. Nutr Cancer. 2019;71(1):61–76. doi: 10.1080/01635581.2018.1557217. Epub 2019 Feb 18.30775929
51 Thomas Berube L, Messito MJ, Woolf K, Deierlein A, Gross R. Correlates of prenatal diet quality in low-income hispanic women. J Acad Nutr Diet. 2019;119(8):1284–1295. doi: 10.1016/j.jand.2019.02.004. Epub 2019 Apr 5.30956126
52 Thomson JL, Tussing-Humphreys LM, Goodman MH, Landry AS. Diet quality in a nationally representative sample of American children by sociodemographic characteristics. Am J Clin Nutr. 2019;109(1):127–138. doi: 10.1093/ajcn/nqy284.30596813
53 Thomson JL, Landry AS, Tussing-Humphreys LM, Goodman MH. Diet quality of children in the United States by body mass index and sociodemographic characteristics. Obes Sci Pract. 2020;6(1):84–98. doi: 10.1002/osp4.388. eCollection 2020 Feb.32128246
54 Todd JE. Revisiting the Supplemental Nutrition Assistance Program cycle of food intake: Investigating heterogeneity, diet quality, and a large boost in benefit amounts. Applied Economic Perspectives and Policy. 2015;37(3):437–458. doi: 10.1093/aepp/ppu039
55 Tovar A, Risica PM, Ramirez A, . Exploring the provider-level socio-demographic determinants of diet quality of preschool-aged children attending family childcare homes. Nutrients. 2020;12(5). doi: 10.3390/nu12051368.
56 Waehrer G, Deb P, Decker SL. Did the 2009 American Recovery and Reinvestment Act affect dietary intake of low-income individuals? Econ Hum Biol. 2015;19:170–183. doi: 10.1016/j.ehb.2015.08.006. Epub 2015 Aug 29.26414481
57 Wang M, Levi R, Seligman H. New SNAP eligibility in california associated with improved food security and health. Prev Chronic Dis. 2021;18:E28. doi: 10.5888/pcd18.200587.33793394
58 Weatherspoon DD, Miller SR, Steele ME, . What social, program, and behavioral factors influence the healthy eating index for EFNEP and SNAP-Ed adult participants? Am J Lifestyle Med. 2017;11(4):344–353. doi: 10.1177/1559827615607194. eCollection 2017 Jul-Aug.30202353
59 Weinfield NS, Borger C, Gola AA. Breastfeeding duration in a low-income sample is associated with child diet quality at age three. J Hum Lact. 2021;37(1):183–193. doi: 10.1177/0890334420903029. Epub 2020 Feb 24.32091965
60 Wilcox S, Sharpe PA, Liese AD, Dunn CG, Hutto B. Socioeconomic factors associated with diet quality and meeting dietary guidelines in disadvantaged neighborhoods in the Southeast United States. Ethn Health. 2020;25(8):1115–1131. doi: 10.1080/13557858.2018.1493434. Epub 2018 Jul 2.29966432
61 Wilson MD, Ramírez AS, Arsenault JE, Miller LMS. Nutrition label use and its association with dietary quality among latinos: the roles of poverty and acculturation. J Nutr Educ Behav. 2018;50(9):876–887. doi: 10.1016/j.jneb.2018.05.019.30297015