# Chapter 1 What is the relationship between income and prices for food items/baskets?

## Specific methods to conduct this rapid review

### Develop a protocol

The research question, “What is the relationship between income and the price of food items/baskets?”, was answered using a rapid review that was informed by an evidence scan.

The analytic framework for the rapid review examining the relationship between income and prices for food items/baskets is presented in Figure 1-a. This analytic framework visually represents the overall scope of the rapid review question and depicts the contributing elements that were examined and evaluated. The intervention or exposure of interest is income (e.g., household, city, regional income) and socioeconomic and geographic proxies for income in U.S. households or populations. The comparators are different levels/categories of income or socioeconomic factor proxy or different geographic areas. The outcomes are the difference in prices of similar food items/baskets of similar items (e.g., jar of spaghetti sauce, unit of banana) in U.S. households or populations. The key confounders are seasonal differences, urban versus rural areas, and cultural/racial diversity or disparities. The other factors to be considered are cultural food choices and neighborhood characteristics (access to healthy foods/distance to store/access to car/type of store). The confounders and other factors to be considered may impact the relationships of interest.

An evidence scan was conducted before the rapid review, and it included any paper that described socioeconomic status (SES) or geographic region for the intervention/exposure. The evidence scan also included education, time (e.g., cooking time), and neighborhood characteristics as key confounders. Based on the evidence scan, the following updates were made to the analytic framework for the rapid review:

- SES and geographic region had to relate directly to income to meet the inclusion criteria for the intervention/exposure.
- Because education is so closely linked to SES, and often included in indices of SES, it was not included as a key confounder in the present rapid review.
- While time (e.g., cooking time) may relate to income and/or food price, it was addressed in a separate rapid review presented in -. Therefore, time was not included as a key confounder in the present rapid review.
- Neighborhood characteristics, including access to foods, were determined to relate to income and/or food price, but were beyond the scope of the present rapid review. Therefore, neighborhood characteristics were not included as a key confounder in the present rapid review.

Further clarifications were made for the rapid review based on the evidence scan, although this did not change the analytic framework or inclusion/exclusion criteria:

- The price of alcoholic beverages does not meet the outcome criterion of “food price” because SNAP funds cannot be spent on alcohol.
- The Nutrition Environment Measures Survey in stores (NEMS-S) tool did not meet the outcome criteria because the price subscore compares price of “regular” foods versus healthy alternatives but does not include food prices.

Figure 1-a Analytic Framework for the rapid review on income and price of food

### Search for and select studies

NESR analysts worked jointly with NEAT staff to establish the final inclusion and exclusion criteria, which are detailed in Table 1-a.

Table 1-a Inclusion and exclusion criteria for the rapid review on income and price of food

Category | Inclusion Criteria | Exclusion Criteria
Study design | - Any study design that is not a narrative review, systematic review, or meta-analysis | - Narrative reviews; - Systematic reviews; - Meta-analyses
Intervention/exposure | - Income (e.g., household, city, regional income); socioeconomic factor proxy for income (e.g., education); geographic area proxy for income | - Socioeconomic factors or geographic areas that are not a direct proxy for income determined by the author
Comparator | - Different levels or categories of income or SES factor proxy for income; - Higher vs. lower geographic areas | - N/A; - Comparison of geographic areas without a proxy for income
Outcomes | - Difference in price of similar food item/basket of similar food items (food items include food item or food category); - Difference in price of basket of similar food items | - Total food/grocery expenditures
Publication date | - Published January 1995 – February 2021 with data from January 1995 – February 2021 | - Before January 1995, after February 2021; - Data prior to January 1995
Publication status | - Articles that have been peer-reviewed; - Grey literature: reports that have not been peer-reviewed but are reports available from government and nongovernmental organizations (e.g., National Bureau of Economic Research) | - Articles that have not been peer-reviewed and are not published in peer-reviewed journals, other than reports from government and nongovernmental organizations
Language | - Articles published in English | - Articles published in languages other than English
Country | - Studies conducted in the U.S. | - Studies conducted outside the U.S.
Study participants | - Human participants | - Non-human participants (e.g., animal studies, in-vitro models)

The final search terms for all databases as well as documentation included in the total, raw search results from each database, as well as search results after removal of duplicates are included in Appendix 1-a. Literature search strategy.

The following outlines any departures from the screen and select studies project methods for this specific rapid review.

- Screening was done at 2 levels. The first level of screening was done using only the title and abstract of each article. If an article was not excluded, it moved forward to the 2^nd^ level, where the full text of the article was screened. After NESR analysts completed screening of both levels, the analysts reconciled any discrepancies between the 2 screenings for the 20 percent of articles which were dual screened. If necessary, a third analyst was consulted to resolve differences.
- Based on the literature, NESR analysts updated the analytic framework to include “type of store” as a commonly-reported measure of the other factor to be considered, “access to healthy foods.”

The compiled list of the included citations, can be found in the References section.

### Extract data and assess the risk of bias

NESR analysts extracted and summarized data from each included article to objectively describe the body of evidence available to answer a rapid review question or inform an evidence scan. The following outlines any departures from the project methods for this specific rapid review:

- Data extraction by single analyst, with quality control conducted by a 2^nd^ analyst. Reconciliation was completed as needed
- Data extracted in Distiller, including author, year of data collection and data source for exposure and outcome, study design, analytic N, geographic location, population description, intervention/exposure and comparator descriptions, outcome description, results, key confounders
- Standard NESR risk of bias forms used in Distiller (dual, independent risk of bias)

### Synthesize the evidence

Evidence synthesis was completed by describing the evidence and evaluating the included studies individually and collectively as previously described in the project methods.

### Summary statements

NESR analysts formed summary statements, as previously described in the project methods, outlining the themes observed during the data synthesis of studies examining income and price of food.

### Recommend future research

Recommendations for future research evaluating the relationship between income and the price of food were determined based on the gaps and limitations observed during data extraction and synthesis, as previously described in the project methods. Future work addressing these gaps and limitations may contribute to the body of evidence available to answer this research question.

## Results

### Literature search and screening results

The literature search yielded 7,313 search results after the removal of duplicates (see Figure 1-b). Dual-screening resulted in the exclusion of 7,043 titles/abstracts and 274 full-texts articles. Reasons for full-text exclusion are in Appendix 1-b. Eight additional articles were identified from the manual search. The body of evidence included 37 articles from 32 studies (31 cross-sectional studies^1–36^ and 1 prospective cohort study^37^). The included articles are listed in Table 1-b.

Evidence was provided for each food group, and most studies evaluated price data from multiple food groups:

- Fruits and Vegetables: 23 studies^1–5,7,9,12–19,22,23,25,27,29,30,32,33,35,36^
- Market Baskets: 11 studies^2,6,8,9,11,18,20,22–24,27,34,37^
- Dairy: 11 studies^1,7,10,14,18,22,23,26,27,29–32^
- Grains: 8 studies^1,7,14,18,22,23,29,30,32^
- Proteins: 2 studies^14,23^

Studies also reported prices of beverages (e.g., energy drinks, sports drinks, ready-to-drink tea and coffee), salty snacks, and sweets (e.g., sugar-sweetened beverages, ice cream), but were not specifically examined in this rapid review.

Figure 1-b Literature search and screen flowchart for the rapid review on income and price of food

### Fruits and vegetables

#### Description of the evidence

##### Population

Twenty-three cross-sectional studies reported fruit and/or vegetable outcomes as individual foods or food group(s), including 19 studies examining price in stores^1–3,7,9,12,13,15,16,18,19,22,23,25,27,29,30,32,35,36^ (N=6^1^ to 1953^27^ stores), and 4 examining prices purchased by households^4,5,14,17,33^ (N=90^17^ to 43,000^14^ households). The body of evidence included samples from across the U.S. and 3 household studies had nationally representative samples.^4,5,14,33^ Five studies that examined prices in stores included small or convenience stores.^7,13,15,32,35^

Thirteen of the studies^3,7,9,12,15,16,18,19,22,23,30,32,35,36^ examined the price of fruit alone as individual foods or food group(s) in stores. No studies examined the price of fruit alone in households.

Twelve of the studies^1,3,9,12,13,16,18,19,22,30,32,35,36^ reported the price of vegetables alone as individual foods or food group(s) in stores and two^14,33^ in households.

##### Intervention/exposure

Thirteen studies^1,4,5,9,13–18,22,23,29,33,36^ measured income, 7 studies^2,3,7,19,25,30,32^ measured geographic location as a proxy for income, and 3 studies^12,26,27,35^ measured a socioeconomic proxy for income.

Of the 13 studies of fruit, 6 studies^9,15,16,18,22,23,36^ measured income, 5 studies^3,7,19,30,32^ measured geographic proxies of income, and 2 studies^12,35^ measured socioeconomic proxies of income.

Of the 14 studies of vegetables, 8 studies^1,9,13,14,16,18,22,33,36^ measured income, 4 studies^3,19,30,32^ measured geographic proxies of income, and 2 studies^12,35^ measured socioeconomic proxies of income.

##### Outcome

Outcomes included prices of fruit (apples, bananas, berries, fruit juice, grapefruit, grapes, lemons, limes, mangoes, melons, oranges, peaches, pears, pineapple, plums, strawberries, total fruit), prices of vegetables (asparagus, avocados, beans, broccoli, cabbage, carrots, cauliflower, celery, corn, cruciferous vegetables, cucumbers, eggplant, green beans, greens, lettuce, mushrooms, okra, onions, peppers, potatoes, squash, tomatoes, frozen vegetables, total vegetables), prices of fruits and vegetables combined, and prices of produce.

#### Synthesis of the evidence

##### Higher income related to higher prices of fruits and vegetables

Among the studies of income and prices paid by households, 3 studies^4,17,33^ of households found a statistically significant relationship between income and price of fruits and vegetables: households with higher incomes tended to pay higher prices for fruits and vegetables compared to households with lower incomes. The effect size ranged from less than 1 cent price index difference between poverty groups to 2 to 3 cents per ounce or cup.

Of the 19 studies examining prices of fruits and vegetables in stores, 14 studies^1,3,7,9,12,13,16,22,23,25,27,32,35,36^ found a statistically significant relationship between income and price: prices of fruits and vegetables were higher in stores located in neighborhoods with higher incomes compared to stores located in neighborhoods with lower incomes. The evidence included samples from states across the U.S. and 4 studies in stores explicitly included small or convenience stores.^7,13,32,35^ Two studies^12,32^ were relatively small (less than 50 stores) and had critical ratings for risk of bias due to exposure classification (Table 1-c); thus the studies could not provide useful information on the relationship between income and price.

Seven studies that examined prices in stores^3,7,9,12,22,23,32^ (N = 25^9^ to 65 stores^7^) reported a statistically significant relationship between income and the prices of fruits alone: prices were higher in stores located in neighborhoods with higher incomes compared to stores located in neighborhoods with lower incomes. All but 1 study^32^ included groceries or supermarkets and 2 studies^7,32^ included convenience stores. Stores were located in the southern and eastern U.S.

One^33^ of the two studies of income and prices paid by households for vegetables found statistically significant relationship, such that households with higher incomes paid higher prices for vegetables compared to households with lower incomes. The study was nationally representative and included 7,143 households. Eight studies in stores^1,9,12,13,16,32,35,36^ (N = 6^1^ to 364 stores^36^) reported a statistically significant finding that stores in higher income neighborhoods had higher vegetable prices than stores in lower income neighborhoods. Three studies^13,32,35^ included convenience stores, and all others included groceries or supermarkets. Stores were primarily located in New York and in the southern and midwestern U.S.

##### Higher income related to lower prices of fruits and vegetables

One study of households^5^ found a small, but statistically significant, relationship between income and price of fruits and vegetables: households with higher incomes paid lower prices for fruits and vegetables.

Five studies^12,16,19,30,35^ found a statistically significant relationship between income and price of fruits and vegetables in stores. Stores located in neighborhoods with higher incomes had lower prices of fruits and vegetables than stores located in neighborhoods with lower incomes. One study^19^ took place exclusively in low-income neighborhoods and another^35^ included only small or non-traditional stores. Two studies^12,19^ had critical ratings for risk of bias due to exposure classification (Table 1-c) and thus could not provide useful information on the relationship between income and price.

Two studies in stores (N = 32^30^ to 1,474 stores^19^) reported a statistically significant relationship between income and the prices of fruits alone, such that stores in higher income neighborhoods had lower fruit prices than stores in lower income neighborhoods. Additionally, four studies in stores (N = 23^16^ to 1,474 stores^19^) reported a statistically significant finding that stores in higher income neighborhoods had lower prices of vegetables compared to stores in lower income neighborhoods. Store types were mixed and were located in California, New York, and Texas.

##### Non-significant associations between income and prices of fruits and vegetables

Two studies^4,14^ found no relationship between income and the price households paid for fruits and vegetables among adolescents (not children)^4^ or for dried beans/peas.^14^

Fifteen studies^2,3,7,9,12,13,15,16,18,19,22,29,30,32,35,36^ found no relationship between income and the price of fruits and vegetables in stores. Although none of the studies were nationally representative, results overall cover much of the country. Six studies^2,7,13,15,32,35^ included convenience or small stores explicitly. Three studies^12,19,32^ had critical ratings for risk of bias due to exposure classification (Table 1c) and thus could not provide useful information on the relationship between income and price.

Nine studies in stores^7,12,15,16,18,30,32,35,36^ (N = 23^16^ to 364 stores^36^) found no relationship between income and the prices of fruits alone. Four studies^7,15,32,35^ included small or convenience stores. Stores were located in the southern and eastern U.S.

One^14^ of the two studies of income and prices paid by households for vegetables found no relationship. The study was nationally representative and included 43,000 households. Seven studies in stores^3,13,16,18,19,22,30,35^ (N = 23^16^ to 1,474 stores^19^) reported no relationship between income and the prices of vegetables alone. Two studies^13,35^ included convenience stores, and overall the studies were distributed across the U.S.

#### Assessment of the evidence

##### Risk of bias

The body of evidence was comprised of cross-sectional studies, with moderate to serious concerns of risk of bias. While the studies generally had low risk of bias related to selection of participants into the study, deviations from intended exposures, and measurement of the outcomes, other domains had generally higher risk of bias. The major concerns are listed below, which limited the ability to draw clear summary statements:

- Most of the studies^1–5,7,9,12,14–19,22,23,25,27,29,30,32,33,35,36^ did not account for all key confounders, resulting in a serious risk of bias.
- The studies of stores had risk of bias related to the exposure classification because each study examined the exposure of income levels of neighborhoods near the stores, but could not provide evidence that residents of those neighborhoods in fact shopped at the study stores and thus may not have faced the food prices in those stores. The risk of bias was critical in 3 studies^12,19,32^.
- Concerns emerged regarding risk of bias due to potential selection of reported results because none of the studies had pre-registered data analysis plans. However, given that the reported domains were generally consistent with reported methods and that most of the studies reported at least 1 non-statistically significant result, the risk was judged to be moderate.
- Several studies^12,15,25,29,30,32,35^ had missing data that differed between exposure groups, often due to a lack of availability of certain foods or food groups in 1 exposure group, resulting in risk of bias due to missing data. Another 3 studies^1,14,33^ did not provide sufficient information to evaluate risk of bias due to missing data.

##### Consistency

Results were inconsistent for the relationship between income and the price of fruits, vegetables, and fruits and vegetables combined, but overall suggest a direct relationship. Results were less clear when examining individual foods, but this may be due to the variety of individual foods examined which did not necessarily overlap across studies. Within studies of households or stores, the methods were generally similar across studies.

Some studies noted that access to larger stores and/or purchasing behaviors explained prices more than income; more of the studies that adjusted for key confounders and store type/access seemed to find no relationship between income and price.

##### Precision

There was an adequate number of studies to investigate the relationship between income and prices of fruits and vegetables, and the studies generally had medium to large sample sizes.

##### Directness

Although multiple studies were designed to examine a different outcome (e.g., diet quality, obesity, or differences in access to stores), they directly examined the relationship between income and price of fruits and vegetables. Some studies reported that store size and/or shopping behavior may explain pricing more than income. Further, most of the studies evaluated prices in stores, which made it difficult to answer the review question because the studies could not prove that neighborhood income was measured in the same individuals who purchased food at the study stores.

##### Generalizability

Overall the body of evidence was geographically diverse, particularly for the results of vegetables and fruits and vegetables combined, and thus the results were generalizable to the U.S. population. This was most clear in the household studies, which were nationally representative; and, the studies in stores were also conducted across the U.S. For the results of fruits there were no nationally representative studies but results overall cover much of the country. There was some racial, ethnic, and socioeconomic diversity across the body of evidence.

### Market baskets

#### Description of the evidence

##### Population

Ten cross-sectional studies^2,6,8,9,11,18,20–24,26,27,34^ and 1 prospective cohort study^37^ reported market basket outcomes. These included 2 studies examining prices purchased by households (N=3,473^37^ to 40,000^8^) and 9 studies examining price^2,6,9,11,18,20–24,26,27,34^ in stores (N=4^20^ to 1,953^27^). The body of evidence included samples from across the U.S. One study explicitly included small or convenience stores.^2^

##### Intervention/exposure

Four studies^8,9,18,22–24^ measured income, 6 studies^2,6,11,20,21,34,37^ measured geographic location as a proxy for income, and 1 study^26,27^ measured a socioeconomic proxy for income.

##### Outcome

All market baskets included foods from multiple food groups. Two studies^8,23^ measured the cost of all foods purchased, 4^9,20–22^ measured the cost of a USDA Market Basket meeting the Dietary Guidelines for Americans, and 4^6,9,11,22,24^ measured the cost of a diet based on the Thrift Food Plan. Three studies^2,18,26,27^ reported the prices of regular and healthier food options of market baskets and two studies^34,37^ simply reported foods across multiple food categories.

#### Synthesis of the evidence

##### Higher income related to higher prices of market baskets

Both studies of households^8,37^ found a statistically significant relationship between income and price of market baskets: higher income households paid more for market baskets than lower income households. The data were from households across the country, with large sample sizes (N=3,473 to 43,000). Five studies^2,6,9,18,24^ reported a statistically significant relationship between income and price of market baskets in stores (N=25^9,24^ to 110 stores^6^), such that stores in higher income neighborhoods had higher prices than stores in lower income neighborhoods. The studies took place primarily in California and in southern, eastern, and midwestern states. One study^2^ explicitly included convenience stores.

##### Higher income related to lower prices of market baskets

Three studies of stores^20,21,27,34^ found a statistically significant finding that price of market baskets was lower in stores from higher versus lower income neighborhoods (N=4^20^ to 1,953^27^). The data were collected from across the U.S. None of the studies explicitly included small or convenience stores.

##### Non-significant associations between income and prices of market baskets

Six studies of stores^2,11,18,22,23,27,34^ reported no relationship between income and the prices (N=55^11^ to 1,953^27^). The data were collected from across the U.S., and 1 study^2^ explicitly included convenience stores.

#### Assessment of the evidence

##### Risk of bias

The body of evidence was comprised primarily of cross-sectional studies with moderate to serious concerns of risk of bias. The studies generally had low risk of bias related to selection of participants into the study, deviations from intended exposures, and measurement of the outcomes. The major concerns in other domains are listed below, which limited the ability to draw clear summary statements:

- Two studies had serious^21,37^ ratings for deviations from intended exposures due to unbalanced co-exposures between exposure groups.
- Most of the studies^2,6,9,11,20,21,23,24,34^ did not account for all key confounders, resulting in a serious risk of bias.
- The studies of stores had risk of bias related to the exposure classification because each study examined the exposure of income levels of neighborhoods near the stores, but could not provide evidence that residents of those neighborhoods in fact shopped at the study stores and thus may not have faced the food prices in those stores. The risk of bias was critical in 2 studies.^21,32^
- Concerns emerged regarding risk of bias due to potential selection of reported results because none of the studies had pre-registered data analysis plans. However, given that the reported domains were generally consistent with reported methods and that most of the studies reported at least 1 non-statistically significant result, the risk was judged to be moderate.
- One study^8^ did not provide sufficient information to evaluate risk of bias due to missing data.

##### Consistency

Results were inconsistent, but generally suggested a relationship between higher income and higher price of market baskets. Methods were generally similar across studies. Many studies noted that access to larger stores and/or purchasing behaviors explained prices more than income.

##### Precision

There was an adequate number of studies to investigate the relationship between income and prices of market baskets, with mostly medium or large sample sizes.

##### Directness

Multiple studies were designed to examine a different outcome (e.g., diet quality, obesity, or differences in access to stores), but still directly examined the relationship between income and price of market baskets. Some studies reported that store size and/or shopping behavior may explain pricing more than income. Further, most of the studies evaluated prices in stores, which made it difficult to answer the review question because the studies could not prove that neighborhood income was measured in the same individuals who purchased food at the study stores.

##### Generalizability

Overall, the body of evidence was geographically diverse, with more studies in urban than in rural areas, and included large, nationally representative studies. There was some racial, ethnic, and socioeconomic diversity across the body of evidence. Therefore, these studies were generalizable to the U.S. population.

### Dairy

#### Description of the evidence

##### Population

Eleven cross-sectional studies reported dairy outcomes, including 10 studies examining price in stores^1,7,10,18,22,23,26,27,29–32^ (N=6^1^ to 8,793^31^ stores), and 1 examining prices purchased by 43,000 households^14^ households). The body of evidence included samples from across the U.S., including two studies with nationally representative data.^26,27,31^

##### Intervention/exposure

Six studies^1,14,18,22,23,29,31^ measured income, 4^7,10,30,32^ measured geographic location as a proxy for income, and 1 study^26,27^ measured a socioeconomic proxy for income.

##### Outcome

Outcomes included milk, cheese, and total dairy.

#### Synthesis of the evidence

##### Higher income related to higher prices of dairy

Four studies found a statistically significant relationship between income and the price of milk^1,10,26^ or low-fat dairy^22^ in grocery stores, such that prices were higher in stores in higher income neighborhoods than in lower income neighborhoods. Study sample sizes ranged from small (N=6)^1,10^ to large (N=1,743).^26^ The study by Kern et al.^26^ was nationally representative.

##### Higher income related to lower prices of dairy

Three studies^10,27,31^ including 2 nationally representative studies,^27,31^ reported a statistically significant between income and price of milk or dairy measured at grocery stores: prices of milk and dairy were higher in stores in higher income neighborhoods than stores in lower income neighborhoods. Study sample sizes ranged from small (N=6)^10^ to large (N=8,793).^31^

##### Non-significant associations between income and prices of dairy

The study of households^14^ found no relationship between income and the price of milk or cheese. Six studies^7,18,22,23,29,30,32^ found no relationship between income and the price of dairy, specifically milk, measured in stores. Study sample sizes ranged from 28^32^ to 73^29^ stores, mostly from New York and the southern U.S. Two studies^7,32^ included convenience stores, and 1 of those^32^ had a critical rating for risk of bias due to exposure classification (Table 1-c) and thus could not provide useful information on the relationship between income and price of milk or cheese.

#### Assessment of the evidence

##### Risk of bias

The body of evidence was comprised of cross-sectional studies with generally moderate to serious concerns of risk of bias. The studies generally had low risk of bias related to selection of participants into the study, deviations from intended exposures, and measurement of the outcomes. The major concerns in other domains are listed below, which limited the ability to draw clear summary statements:

- Most of the studies^1,7,10,14,23,29–32^ did not account for all key confounders, resulting in a serious risk of bias.
- The studies of stores had risk of bias related to the exposure classification because each study examined the exposure of income levels of neighborhoods near the stores, but could not provide evidence that residents of those neighborhoods shopped at the study stores and thus may not have faced the food prices in those stores. The risk of bias was critical in 1 study.^32^
- Concerns emerged regarding risk of bias due to potential selection of reported results because none of the studies had pre-registered data analysis plans. However, given that the reported domains were generally consistent with reported methods and that most of the studies reported at least 1 non-statistically significant result, the risk was judged to be moderate.
- Three studies^29,30,32^ had missing data that differed between exposure groups, often due to a lack of availability of certain foods or food groups in 1 exposure group, resulting in risk of bias due to missing data. Another 2 studies^1,14^ did not provide sufficient information to evaluate risk of bias due to missing data.

##### Consistency

Results were inconsistent for the relationship between income and the price of dairy, with generally similar methods across studies. Specific food items studies varied across studies. Many studies noted that access to larger stores and/or purchasing behaviors explained prices more than income.

##### Precision

There were an adequate number of studies to investigate the relationship between income and prices of dairy, with varied sample sizes.

##### Directness

Multiple studies were really designed to examine a different outcome (e.g., diet quality, obesity, or differences in access to stores), but still directly examined the relationship between income and price of dairy. Some studies reported that store size and/or shopping behavior may explain pricing more than income. Further, most of the studies evaluated prices in stores, which made it difficult to answer the review question because the studies could not provide evidence that neighborhood income was measured in the same individuals who faced food prices at the study stores.

##### Generalizability

Overall the body of evidence was fairly geographically diverse, and included large, nationally representative studies. There was some racial, ethnic, and socioeconomic diversity across the body of evidence. Therefore, these studies were generalizable to the U.S. population.

### Grains

#### Description of the evidence

##### Population

Eight cross-sectional studies reported grains as individual foods or food group(s), including 7 studies examining price in stores^1,7,18,22,23,29,30,32^ (N=6^1^ to 73^29^ stores), and 1 examining prices purchased by 43,000 households.^14^ The body of evidence included samples from across the U.S. Two studies in stores included small or convenience stores.^7,32^

##### Intervention/exposure

Five studies^1,14,18,22,23,29^ measured income and 3^7,30,32^ measured geographic location as a proxy for income. No studies measured a socioeconomic proxy for income.

##### Outcome

Outcomes included bread, breakfast cereals, flour, oatmeal, pasta, rice, and whole grains.

#### Synthesis of the evidence

##### Higher income related to higher prices of grains

Three studies^1,18,32^ found a statistically significant relationship suggesting that higher income was related to higher grains prices, but the results were difficult to interpret. In 1 study,^1^ prices did not differ between neighborhoods, shoppers in higher income neighborhoods purchased more expensive grains than shoppers in lower-income neighborhoods, suggesting that the effects reflected consumer behavior rather than prices faced. In a 2^nd^ study,^18^ prices of more nutrient dense grains were reported in comparison to less nutrient dense grains, and the size of the store was a stronger determinant of relative price than income. Further, the third study^32^ had critical ratings for risk of bias due to exposure classification (Table 1-c) and thus could not provide useful information on the relationship between income and price of grains.

##### Higher income related to lower prices of grains

Two studies of stores reported a statistically significant relationship between income and the price of bread^30^ and cereal^23^: stores in higher income neighborhoods had higher prices than stores in lower neighborhoods.

##### Non-significant associations between income and prices of grains

One study of 43,000 households across the U.S.^14^ found no relationship between income and the price of grains, specifically the price of ready-to-eat breakfast cereal. Six studies in stores^1,7,18,22,23,29,32^ found no relationship between income and the price of grains, specifically the price of whole grain bread.^7,18,23,29,32^ Sample sizes ranged from 6^1^ to 73^29^ stores, and 2 of the studies^7,32^ included data from convenience stores. Stores were primarily located in the southern and eastern U.S.

#### Assessment of the evidence

##### Risk of bias

The body of evidence was comprised of cross-sectional studies with generally moderate to serious concerns of risk of bias. While the studies generally had low risk of bias related to selection of participants into the study, deviations from intended exposures, and measurement of the outcomes, other domains had generally higher risk of bias. The major concerns are listed below, which limited the ability to draw clear summary statements:

- Most of the studies^1,7,14,23,29,30,32^ did not account for all key confounders, resulting in a serious risk of bias.
- The studies of stores had serious risk of bias related to the exposure classification because each study examined the exposure of income levels in neighborhoods near the stores but did not provide evidence that residents of those neighborhoods shopped at the study stores. The risk of bias was critical in 1 study because the exposure was not clearly defined.^32^
- Risk of bias due to potential selection of reported results was possible because none of the studies had pre-registered data analysis plans. However, the risk was judged to be moderate because the reported domains were generally consistent with reported methods and that most of the studies reported at least 1 non-statistically significant result.
- Three studies^29,30,32^ had missing data that differed between exposure groups, often due to a lack of availability of certain foods or food groups in 1 exposure group, resulting in risk of bias due to missing data. Two additional studies^1,14^ did not provide sufficient information to evaluate risk of bias due to missing data.

##### Consistency

Results were inconsistent for the relationship between income and the price of grains, with little overlap in the specific foods studied. Within studies of households or stores, respectively, the methods were generally similar across studies. Some studies noted that access to larger stores and/or purchasing behaviors explained prices more than income; more of the higher-quality studies reported no relationship between income and price.

##### Precision

There were a somewhat small number of studies to investigate the relationship between income and grain prices, and the studies generally had small to medium sample sizes.

##### Directness

Most of the studies reported that store size and/or shopping behavior may explain pricing more than income. Further, most of the studies evaluated prices in stores, which made it difficult to answer the review question because the studies could not prove that neighborhood income was measured in the same people who purchased food at the study stores.

##### Generalizability

There were concerns with generalizability of the evidence as most studies were conducted in the eastern and midwestern regions of the U.S., and studies did not report sufficient information to evaluate the racial, ethnic, and socioeconomic diversity across the body of evidence.

### Proteins

#### Description of the evidence

##### Population

Two cross-sectional studies reported protein food outcomes, including 1 study examining price in stores^23^ (N=57 stores), and 1 examining prices purchased by households^14^ (N=43,000 households). Hayes et al.^23^ was conducted in New York City and Davis et al.^14^ had a nationally representative sample.

##### Intervention/exposure

Both studies^14,23^ measured income. No studies measured either geographic or socioeconomic proxies for income.

##### Outcome

Outcomes included chicken, eggs, ground beef, peanut butter, and tuna.

##### Synthesis of the evidence

There was insufficient evidence to examine the relationship between income and price of protein foods.

## Summary statements and research recommendations

### Summary statements

The findings of the rapid review are presented in the following summary statements.

##### Fruits and vegetables

Evidence suggests that a higher income may be associated with a higher price of vegetables and fruits and vegetables combined, but shopping behavior may be an important factor in interpreting the data.

Evidence suggests no relationship between income and price of fruit, although higher income may be associated with a higher price of fruit. Store size and/or shopping behavior may explain pricing more than income.

All studies were cross-sectional, resulting in risk of bias concerns common in that study design. Most of the studies did not account for all key confounders and had risk of bias related to the exposure classification because most studies did not measure the exposure and outcome for the same individuals.

##### Market baskets

Evidence indicates that a higher income is associated with a higher price of market baskets. Income was more strongly associated with shopping behaviors and store size/access than the actual prices faced, although shopping behavior may be in response to prices.

Most of the studies did not account for all key confounders and had risk of bias related to the exposure classification because most studies did not measure the exposure and outcome for the same individuals.

##### Dairy

Evidence suggests that a higher income may be weakly associated with a lower price of dairy products, although studies were not consistent. Income was more strongly associated with shopping behaviors and store size/access than the actual prices faced, although shopping behavior may be in response to prices.

All studies were cross-sectional, resulting in risk of bias concerns common in that study design. Most of the studies did not account for all key confounders and had risk of bias related to the exposure classification because most studies did not measure the exposure and outcome for the same individuals.

##### Grains

Evidence suggests no relationship between income and price of grains, particularly whole-grain breads. There was not enough evidence to examine the relationship with other types of grains. Store size and or shopping behavior may explain pricing more than income.

All studies were cross-sectional, resulting in risk of bias concerns common in that study design. Most of the studies did not account for all key confounders and had risk of bias related to the exposure classification because most studies did not measure the exposure and outcome for the same individuals.

##### Protein foods

There was not enough evidence to examine the relationship between income and price of protein foods.

## Research recommendations

1. Conduct well-designed, longitudinal studies that examine the relationship between income and food price over time. In particular, these studies should directly examine the relationship between household-level income and actual prices at stores where household members shop for food.
2. Assess income exposures using standard definitions and categories to improve comparability across studies.
3. Assess food group prices using standard definitions and categories to improve comparability across studies.
4. Differentiate between participants in Federal assistance programs who are income-eligible, income-eligible nonparticipants, and income-ineligible nonparticipants.
5. Account for store size/type, access to stores, as well as other potential confounders including urban versus rural setting and cultural/racial diversity or disparities, to better determine the response to income on food price as a function of these factors.

Table 1-b Evidence examining the relationship between income and price^a^

Article | Study and Participant Characteristics | Intervention | Outcome(s) | Results
Prospective cohort study
Colabianchi, 2021 ^37^ | N=3473; All participants lived in public housing or project-based assisted housing located centrally in 1 of the five cities in a census tract with high poverty rates (i.e., 40% or more persons in the census tract had incomes < federal poverty threshold) in 1995-1998. | Geographic location; - Treatment; - Section 8; - Control | Market basket | Direct relationship, Statistically significant; Mean (log transformed), SE price per unit averaged across 13 categories, weighted linear regression, F-statistic: 16.50, p<0.001; Treatment (n=1428): 0.30, 0.026; Section 8 (n=982): 0.24, 0.030; Control (n=1063): 0.07, 0.031
Cross-sectional studies
Akbay, 2005 ^1^ | N=6; Analytic N is stores (supermarkets); Columbus, Ohio metropolitan area | Income; - Lower; - Higher | Breakfast cereals | Direct relationship, Statistically significant; Mean price paid for food products, cents per ounce; Breakfast cereals, t-test; Private brand price; Lower income: 14.16; Higher income: 14.73; t: −4.72; p<0.01; National brand price; Lower income: 20.02; Higher income: 21.29; t: −11.60; p<0.01
| | | Cooking oil | Direct relationship, Statistically significant; Mean price paid for food products, cents per ounce; Cooking oil, t-test; Private brand price; Lower income: 6.99; Higher income: 11.98; t: −25.44; p<0.01; National brand; Lower income: 7.89; Higher income: 15.34; t: −27.88; p<0.01
| | | Ice cream | Direct relationship, Statistically significant; Mean price paid for food products, cents per ounce; Ice cream, t-test; Private brand price; Lower income: 3.50; Higher income: 3.98; t: −11.49; p<0.01; National brand; Lower income: 6.66; Higher income: 9.28; t: −20.95; p<0.01
| | | Mayonnaise | No relationship, Statistically non-significant; Mayonnaise, t-test; Private brand price; Lower income: 6.18; Higher income: 6.28; t: −1.69; p<0.10; National brand; Lower income: 11.29; Higher income: 11.27; t: −0.17; p>0.10
| | | Milk | Direct relationship (National brand), Statistically significant; Mean price paid for food products, cents per ounce; Fluid milk, t-test; Private brand price; Lower income: 1.81; Higher income: 1.85; t: −1.47; p>0.10; National brand; Lower income: 3.33; Higher income: 4.37; t: −22.6; p<0.01
| | | Pasta | Direct relationship (National brand), Statistically significant; Mean price paid for food products, cents per ounce; Pasta, t-test; Private brand price; Lower income: 5.50; Higher income: 5.52; t: −0.72; p>0.10; National brand; Lower income: 8.06; Higher income: 9.14; t: −13.75; p<0.01
| | | Salad dressing | Direct relationship, Statistically significant; Mean price paid for food products, cents per ounce; Salad dressing, t-test; Private brand price; Lower income: 9.67; Higher income: 10.62; t: −8.70; p<0.01; National brand; Lower income: 13.41; Higher income: 17.22; t: −16.51; p<0.01
| | | Salty Snacks | Direct relationship (National brand); Inverse relationship (Private brand), Statistically significant; Mean price paid for food products, cents per ounce; Salty snacks, t-test; Private brand price; Lower income: 13.06; Higher income: 12.65; t: 3.02; p<0.01; National brand; Lower income: 19.60; Higher income: 20.22; t: −5.83; p<0.01
| | | Vegetables | Direct relationship, Statistically significant; Mean price paid for food products, cents per ounce; Frozen vegetables, t-test; Private brand price; Lower income: 8.60; Higher income: 11.61; t: −9.47; p<0.01; National brand; Lower income: 12.51; Higher income: 13.06; t: −4.97; p<0.01
Andreyeva, 2008 ^2^ | N=48, 75; Study 1: Analytic N=48 stores; Supermarkets within a three-mile distance from neighborhoods | Geographic location; - Lower; - Higher | Produce | No relationship, Statistically non-significant; Study 1: Average prices were not significantly different between lower- and higher-income neighborhoods
| Study 2: Analytic N=75 stores (19 small and large grocery stores; 56 convenience stores) | | Healthier Market Basket | Direct relationship, Statistically significant; Study 2: Average prices of healthful food basket, t-test; Low-income area: $26.10; High-income area: $27.20; p<0.05
| | | Market basket | Direct relationship, Statistically significant; Study 2: Average prices of all-foods basket, t-test; Low-income area: $46.70; High-income area: $48.50; p<0.05
| | | Unhealthy food price | Direct relationship, Statistically non-significant; Study 2: Average prices of regular food basket, t-test; Low-income area: $20.60; High-income area: $21.30; p>0.05
Ard, 2010 ^3^ | N=44; Analytic N is grocery stores in Jefferson and Shelby counties; Neighborhood median characteristics:; 29% African American; 80% ≥high school diploma; 12% HH <poverty level | Geographic location; % HH below poverty level | Potatoes | Direct relationship (t-test), Statistically significant; No relationship (multiple linear regression), Statistically non-significant; Price/serving of white potatoes during spring months, multiple linear regression (adjusted for % African American and % ≥ high school diploma); Beta coefficient (SE),; % HH below poverty level: 0.000 (0.001), p=0.92; F (35,3): 4.073, Adjusted R^2^: 0.195; Mean prices for potatoes, t-test, p=0.004; Highest tertile for % below poverty level: $0.09; Lowest tertile for % below poverty level: $0.13
| | | Strawberries | Direct relationship, Statistically significant; Mean price of strawberries, t-test, p=0.048; Middle tertile for % below poverty level: $0.16; Top tertile for % below poverty level: NR but lower than middle tertile
Beydoun, 2008 ^5^ | N=7331; Analytic N is nationally representative sample of 7331 adults from USDA Continuing Survey of Food Intakes by Individuals (CSFII) 1994–1996.; Mean age of 39.8 (SD: 0.25); 13.3 (SD: 1.0) years of education, 51% female, 74% non-Hispanic White; highest proportion lived in the South (36%); 47% lived in suburban areas | Income; - PIR ≤130%; - PIR 131-299%; - PIR ≥300% | Fruits and Vegetables | Inverse relationship, Statistically significant; FV-PI; Weighted Mean (SEM), ANOVA, p<0.05; ≤130% (n=1616): $0.728 (0.009); 131-299% (n=2713): $0.722 (0.007); ≥300% (n=3002): $0.727 (0.007); FV-PI; Weighted Mean (SEM), ANOVA, p<0.05; ≤130%: $0.728 (0.009); 131-299%: $0.722 (0.007); ≥300%: $0.727 (0.007)
Beydoun, 2011 ^4^ | N=8438; Analytic N is nationally representative sample of 6759 children aged 2-9 y and 1679 adolescents age 10-18 y from USDA Continuing Survey of Food Intakes by Individuals (CSFII) 1994–1996 and additional data collected from children aged; 2–9 y in 1998. | Income; - PIR ≤185%; - PIR >185% | Fruits and Vegetables | Direct relationship (Children), Statistically significant; No relationship (Adolescents), Statistically non-significant; FV-PI among children (2-9 y); Weighted Mean (SE), ANOVA, p<0.05; ≤185%: $0.72 (0.01); >185%: $0.73 (0.01); FV-PI among adolescents (10-18 y); Weighted Mean (SE), ANOVA, p≥0.05; ≤185%: $0.72 (0.01); >185%: $0.72 (0.01)
Block, 2006 ^6^ | N=110; Analytic N is stores;; Austin: population 117,527, 42% of the HH lived in homes for ≥10 years. 24% HH<poverty level; primarily African American population with averages lower middle income; Oak Park: population 52,500. Upper-middle-income suburb with a mixed profile | Geographic location; - Austin; - Oak Park | USDA Market Basket | Direct relationship, Statistically significant; Difference of means t-test:; Austin $110 vs. Oak Park $122;; P<0.001
Borja, 2019 ^7^ | N=65; Analytic N is stores, including 25 grocery stores and 40 convenience stores; County population of 1,408,566, 75% White, 18% African American, 29% Hispanic or Latino; Median household income of $51,681 | Geographic location; - low-income areas; - not-low-income areas | Apples | Direct relationship (regression), Statistically significant; No relationship (t-test), Statistically non-significant; Mean prices of apples per unit; T-test, P=NS; Low-income areas: $0.78; Not-low-income areas: $0.79; Beta coefficient (SE), Income and price regression (adjusted for distance, no car, density, and store type); Apple: 0.31 (0.13), p<0.05
| | | Bananas | Direct relationship (regression), Statistically significant; No relationship (t-test), Statistically non-significant; Mean prices of bananas per unit; T-test, P=NS; Low-income areas: $0.39; Not-low-income areas: $0.38; Beta coefficient (SE), Income and price regression (adjusted for distance, no car, density, and store type); Banana: 0.22 (0.11), p<0.05
| | | Bread | Direct relationship, Statistically non-significant; Mean prices for white bread; T-test, P=NS; Low-income areas: $2.73; Not-low-income group: $2.89; Mean prices for whole wheat bread; T-test, P=NS; Low-income areas: $2.85; Not-low-income group: $2.87; Beta coefficient (SE), Income and price regression (adjusted for distance, no car, density, and store type); White bread: −0.02 (0.39), NS; Wheat bread: 0.05 (0.43), NS
| | | Breakfast cereals | No relationship, Statistically non-significant; Mean prices of high sugar content cereal per 17/18 oz box; T-test, P=NS; Low-income areas: $4.44; Not-low-income areas: $4.03; Mean prices of low sugar content cereal per 17/18 oz box; T-test, P=NS; Low-income areas: $3.96; Not-low-income areas: $3.85; Beta coefficient (SE), Income and price regression (adjusted for distance, no car, density, and store type); High sugar content cereal: −0.24 (0.39), NS; Low sugar content cereal: −0.23 (0.34), NS
| | | Milk | No relationship, Statistically non-significant; Mean price of whole milk (1 gallon); T-test, P=NS; Low-income areas: $4.28; Not-low-income areas: $4.02; Mean price of 2%-fat milk (1 gallon); T-test, P=NS; Low-income areas: $4.21; Not-low-income areas: $3.96; Mean price of 1%-fat milk (1 gallon); T-test, P=NS; Low-income areas: $3.79; Not-low-income areas: $3.69; Mean price of skim milk (1 gallon); T-test, P=NS; Low-income areas: $3.73; Not-low-income areas: $3.59; Beta coefficient (SE), Income and price regression (adjusted for distance, no car, density, and store type); Whole milk: 0.05 (0.27), NS; 1% milk: 0.28 (0.28), NS; 2% milk: 0.26 (0.27), NS
| | | Oranges | No relationship, Statistically non-significant; Mean prices of oranges per unit; T-test, P=NS; Low-income areas: $0.88; Not-low-income areas: $0.92; Beta coefficient (SE), Income and price regression (adjusted for distance, no car, density, and store type); Orange: 0.14 (0.16), NS
Broda, 2009 ^8^ | N=40,000; Analytic N is demographically representative households; Analytic N is demographically representative household and 452 stores across the U.S | Income; continuous | Food | Direct relationship, Statistically significant; Ln (Price), Regression, within R^2^: 0.0638; Coefficient (SE), (adjusted for log income in household’s zipcode, log income income in store’s zipcode, household size, age, race, marital status, city of residence, and retail chain controls); Log HH Income: 0.0088 (0.0001), p<0.01; Food, produce not included; Ln (Price), Regression, R^2^: 0.0304; Coefficient (SE), (adjusted for log income in household’s zipcode, log income income in store’s zipcode, race, store type, household size, age, marital status, and city of residence); Log HH Income: 0.0117 (0.0001), p<0.01; Non-random weight foods; Ln (Price), Regression, R^2^: 0.0764; Coefficient (SE), (adjusted for log income in household’s zipcode, log income income in store’s zipcode, household size, age, race, marital status, and city of residence, retail chain controls); Log HH Income: 0.0079 (0.0001), p<0.01; Random weight foods; Ln (Price), Regression, R^2^: 0.0474; Coefficient (SE), (adjusted for log income in household’s zipcode, log income income in store’s zipcode, household size, age, race, marital status, and city of residence, retail chain controls); Log HH Income: 0.0408 (0.0021), p<0.01
Cassady, 2007 ^9^ | N=75; N=75 observations across 25 stores and 3 timepoints; Number of observations by store type (N): Bulk (12), Independent (9), Chain (54) | Income; - Very low; - Low; - Middle; - High | 2005 DGA Market Basket | Direct relationship, Statistically significant; 2005 DGA Market Basket; Mean total cost of F&V, t-test; Very Low : $64.94; Low: $66.67; Middle: $77.82, vs. Very Low p<0.05, vs. Low p<0.05; High: $73.07, vs. Very Low p<0.05, vs. Low p<0.05
| | | TFP Food Basket | Direct relationship, Statistically significant; TFP market basket; Mean total cost of F&V, t-test; Very Low and Low: $65; Middle and High: $78, vs. Very Low and Low p≤0.05
| | | Fruit | Direct relationship (Middle vs. lower), Statistically significant; No relationship (High vs. lower), Statistically non-significant; 2005 DGA Market Basket; Mean cost of fruit, t-test; Very Low: $31.60; Low: $32.84; Middle: $37.62, vs. Very Low p<0.05, vs. Low p<0.05; High: $35.60
| | | Vegetables | Direct relationship, Statistically significant; 2005 DGA Market Basket; Mean cost of vegetables, t-test; Very Low: $33.34; Low: $34.28; Middle: $40.19, vs. Very Low p<0.05, vs. Low p<0.05; High: $37.47, vs. Very Low p<0.05, vs. Low p<0.05, vs. Middle p<0.05; Mean cost of dark green vegetables, t-test, p>0.05; Very Low: $4.41; Low: $4.70; Middle: $4.89; High: $4.63; Mean cost of orange vegetables, t-test; Very Low: $1.60; Low: $1.76; Middle: $2.33, vs. Very Low p<0.05, vs. Low p<0.05; High: $2.17, vs. Very Low p<0.05, vs. Low p<0.05; Mean cost of legumes, t-test, p>0.05; Very Low: $9.05; Low: $8.58; Middle: $9.66; High: $9.82; Mean cost of starchy vegetables, t-test; Very Low: $2.81; Low: $2.94; Middle: $4.22, vs. Very Low p<0.05, vs. Low p<0.05; High: $3.38; Mean cost of other vegetables, t-test; Very Low: $15.77; Low: $15.84; Middle: $19.09, vs. Very Low p<0.05, vs. Low p<0.05; High: $17.47
| | | Fruit | Direct relationship, Statistically significant; TFP market basket; Mean cost of fruit, t-test, Data NR
| | | Vegetables | Direct relationship, Statistically significant; TFP market basket (Prices NR); Mean cost of vegetables; High more than Very Low and Low, p>0.05; Mean cost of orange vegetables; Middle more than Very Low and Low, p≤0.05; High more than Very Low and Low, p≤0.05; Mean cost of starchy vegetables; Middle more than Very Low and Low, p≤0.05; Mean cost of other vegetables; Middle more than Very Low and Low, p≤0.05
Chang, 2011 ^10^ | N=6; Analytic N is stores; [underlined: Race]:; Inner-city: White: 76.2%, Black: 21.7%, Other: 2.0%; Suburban: White: 93.6%, Black: 3.5%, Other: 3.0%; [underlined: Education]:; Inner-city: 30.4% at least some college, 33.7% did not graduate from high school; Suburban: 65% at least some college, 11.3% did not graduate from high school | Geographic location; - Low Income; - High Income | Milk | Direct relationship (organic milk), Statistically significant; Inverse relationship (conventional skim milk), Statistically significant; Price per half gallon; Mean conventional whole milk prices, t-test, p=0.50; Inner-city: $1.297; Suburban: $1.305; Mean conventional 2% milk prices, t-test, p=0.38; Inner-city: $1.297; Suburban: $1.308; Mean conventional 1% milk prices, t-test, p=0.24; Inner-city: $1.284; Suburban: $1.269; Mean conventional skim milk prices, t-test, p=0.00; Inner-city: $1.363; Suburban: $1.324; Mean organic whole milk prices, t-test, p=0.00; Inner-city: $2.980; Suburban: $3.251; Mean organic 2% milk prices, t-test, p=0.00; Inner-city: $3.117; Suburban: $3.267; Mean organic 1% milk prices, t-test, p=0.00; Inner-city: $3.210; Suburban: $3.411; Mean organic skim milk prices, t-test, p=0.00; Inner-city: $2.877; Suburban: $3.271
Chung, 1999 ^11^ | N=55; N is stores; Nonpoor (n=31): zip codes with <10% below poverty level; 87% of chain stores and 60% of nonchain stores in these ZIP; Poor (n=24): zip codes with ≥10% below poverty level; 13% of chain stores and 40% of nonchain stores in these ZIP | Geographic location; - Poor; - Non-poor | TFP Food Basket | Inverse relationship, Statistically significant; Mean basket price, t-test; Poor: $110.36; Non-poor: $105.21; Difference: $5.15; Difference (adjusted for chains and availability): $3.41; t-value: 1.3076, p>0.10; Recursive model, Adj R^2=0.2535, p=0.0009; Coefficient, t-value; Poor: −1.5223, −0.329 (NS); Adjusted for chain supermarket, % stores in ZIP chains, availability index
Cole, 2010 ^12^ | N=45; Analytic N is census tracts two Brooklyn Community Districts (BCD). BCD 6 included Carroll Gardens, Cobble Hill, Park Slope, Gowanus, and Red Hook. BCD 9 included Crown Heights South, Prospect Lefferts Gardens, and Wingate. | SES proxy; - >80% Black (low income); - 20-80% Black (middle); - <20% Black (high income) | Apples | Direct relationship, Statistically significant; Mean (SD) price of apples, statistical method NR, p=significant; Predominantly Black, low-income (n=3): $0.44 (n/a); Mixed race, middle income (n=7): $0.52 (0.11); Predominantly White, high-income (n=17): $0.70 (0.24)
| | | Asparagus | Direct relationship, Statistically significant; Mean (SD) price of asparagus, statistical method NR, p=significant; Predominantly Black, low-income (n=1): $2.39 (n/a); Mixed race, middle income (n=1): $n/a (n/a); Predominantly White, high-income (n=5): $3.06 (1.01)
| | | Avocados | Direct relationship, Statistically significant; Mean (SD) price of avocados, statistical method NR, p=significant; Predominantly Black, low-income (n=1): $n/a (n/a); Mixed race, middle income (n=6): $1.31 (0.41); Predominantly White, high-income (n=11): $1.79 (0.38)
| | | Bananas | Direct relationship, Statistically significant; Mean (SD) price of yellow bananas, statistical method NR, p=significant; Predominantly Black, low-income (n=0): $n/a (n/a); Mixed race, middle income (n=10): $0.24 (0.06); Predominantly White, high-income (n=18): $0.29 (0.09)
| | | Berries | Direct relationship, Statistically significant; Mean (SD) price of berries, statistical method NR, p=significant; Predominantly Black, low-income (n=1): $3.33 (n/a); Mixed race, middle income (n=5): $3.24 (1.75); Predominantly White, high-income (n=11): $4.10 (1.39)
| | | Broccoli | Direct relationship, Statistically significant; Mean (SD) price of broccoli, statistical method NR, p=significant; Predominantly Black, low-income (n=1): $1.49 (n/a); Mixed race, middle income (n=2): $0.99 (n/a); Predominantly White, high-income (n=7): $2.32 (0.71)
| | | Corn | Direct relationship, Statistically significant; Mean (SD) price of corn, statistical method NR, p=significant; Predominantly Black, low-income (n=1): $n/a (n/a); Mixed race, middle income (n=4): $0.33 (n/a); Predominantly White, high-income (n=8): $0.89 (0.44)
| | | Cucumbers | Direct relationship, Statistically significant; Mean (SD) price of cucumbers, statistical method NR, p=significant; Predominantly Black, low-income (n=1): $0.50 (n/a); Mixed race, middle income (n=6): $0.34 (0.15); Predominantly White, high-income (n=11): $0.55 (0.42)
| | | Eggplant | Direct relationship, Statistically significant; Mean (SD) price of eggplants, statistical method NR, p=significant; Predominantly Black, low-income (n=1): $n/a (n/a); Mixed race, middle income (n=5): $0.63 (0.11); Predominantly White, high-income (n=6): $1.09 (0.36)
| | | Grapefruit | Direct relationship, Statistically significant; Mean (SD) price of grapefruit, statistical method NR, p=significant; Predominantly Black, low-income (n=1): $0.65 (n/a); Mixed race, middle income (n=5): $0.60 (0.24); Predominantly White, high-income (n=12): $1.24 (0.75)
| | | Green beans | Direct relationship, Statistically significant; Mean (SD) price of green beans (lb), statistical method NR, p=significant; Predominantly Black, low-income (n=2): $0.99 (n/a); Mixed race, middle income (n=5): $2.94 (n/a); Predominantly White, high-income (n=9): $2.31 (0.58)
| | | Lemons | Direct relationship, Statistically significant; Mean (SD) price of lemons, statistical method NR, p=significant; Predominantly Black, low-income (n=4): $0.25 (n/a); Mixed race, middle income (n=6): $0.27 (0.04); Predominantly White, high-income (n=15): $0.42 (0.22)
| | | Lettuce | Direct relationship, Statistically significant; Mean (SD) price of greens, lettuce, statistical method NR, p=significant; Predominantly Black, low-income (n=3): $0.99 (n/a); Mixed race, middle income (n=6): $1.35 (0.51); Predominantly White, high-income (n=11): $1.43 (0.96)
| | | Limes | Direct relationship, Statistically significant; Mean (SD) price of limes, statistical method NR, p=significant; Predominantly Black, low-income (n=1): $0.15 (n/a); Mixed race, middle income (n=4): $0.17 (0.05); Predominantly White, high-income (n=14): $0.42 (0.23)
| | | Mangoes | No relationship, Statistically non-significant; Mean (SD) price of mangoes, statistical method NR, p=NS; Predominantly Black, low-income (n=1): $1.50 (n/a); Mixed race, middle income (n=5): $1.47 (0.35); Predominantly White, high-income (n=14): $1.39 (0.47)
| | | Melons | Direct relationship, Statistically significant; Mean (SD) price of melons, statistical method NR, p=significant; Predominantly Black, low-income (n=1): $1.50 (n/a); Mixed race, middle income (n=6): $1.60 (1.12); Predominantly White, high-income (n=10): $3.12 (1.39)
| | | Mushrooms | Direct relationship, Statistically non-significant; Mean (SD) price of mushrooms (lb), statistical method NR, p=NR; Predominantly Black, low-income (n=1): $n/a (n/a); Mixed race, middle income (n=2): $3.39 (n/a); Predominantly White, high-income (n=7): $6.24 (3.20)
| | | Okra | Inverse relationship, Statistically significant; Mean (SD) price of okra (lb), statistical method NR, p=significant; Predominantly Black, low-income (n=1): $3.99 (n/a); Mixed race, middle income (n=2): $2.00 (n/a); Predominantly White, high-income (n=2): $1.54 (1.34)
| | | Oranges | Direct relationship, Statistically significant; Mean (SD) price of oranges, statistical method NR, p=significant; Predominantly Black, low-income (n=3): $0.33 (n/a); Mixed race, middle income (n=6): $0.44 (0.07); Predominantly White, high-income (n=15): $0.56 (0.24)
| | | Pears | Direct relationship, Statistically significant; Mean (SD) price of pears, statistical method NR, p=significant; Predominantly Black, low-income (n=0): $n/a (n/a); Mixed race, middle income (n=5): $0.49 (0.05); Predominantly White, high-income (n=9): $0.76 (0.22)
| | | Peppers | Direct relationship, Statistically significant; Mean (SD) price of peppers, statistical method NR, p=significant; Predominantly Black, low-income (n=1): $0.33 (n/a); Mixed race, middle income (n=7): $0.56 (0.08); Predominantly White, high-income (n=11): $0.94 (0.49)
| | | Pineapple | Direct relationship, Statistically significant; Mean (SD) price of pineapples, statistical method NR, p=significant; Predominantly Black, low-income (n=0): $n/a (n/a); Mixed race, middle income (n=4): $1.99 (n/a); Predominantly White, high-income (n=9): $4.42 (1.13)
| | | Plums | Direct relationship, Statistically significant; Mean (SD) price of plums, statistical method NR, p=significant; Predominantly Black, low-income (n=0): $n/a (n/a); Mixed race, middle income (n=5): $0.34 (0.20); Predominantly White, high-income (n=11): $0.67 (0.30)
| | | Potatoes | Direct relationship, Statistically significant; Mean (SD) price of potatoes, statistical method NR, p=significant; Predominantly Black, low-income (n=6): $0.33 (n/a); Mixed race, middle income (n=9): $0.41 (0.36); Predominantly White, high-income (n=17): $1.01 (1.63)
| | | Squash | Direct relationship, Statistically significant; Mean (SD) price of squash, statistical method NR, p=significant; Predominantly Black, low-income (n=1): $1.00 (n/a); Mixed race, middle income (n=6): $1.00 (0.49); Predominantly White, high-income (n=8): $1.61 (1.30)
| | | Tomatoes | Direct relationship, Statistically significant; Mean (SD) price of , statistical method NR, p=significant; Predominantly Black, low-income (n=3): $0.54 (n/a); Mixed race, middle income (n=7): $0.51 (0.07); Predominantly White, high-income (n=17): $0.77 (0.33)
Daepp, 2015 ^13^ | N=40; Analytic N = stores | Income; - Low; - High | Broccoli | No relationship, Statistically non-significant; Broccoli (bunch) in grocery stores; High vs. Low income; Kruskall Wallis Chi-square: 3.7817, p=0.0518
| | | Cabbage | No relationship, Statistically non-significant; Cabbage (1 lb) in grocery stores; High vs. Low income; Kruskall Wallis Chi-square: 0.9724, p=0.3241
| | | Carrots | No relationship, Statistically non-significant; Carrots (1 lb) in grocery stores; High vs. Low income; Kruskall Wallis Chi-square: 0.3628, p=0.547
| | | Cauliflower | Direct relationship, Statistically significant; Cauliflower (pc) in grocery stores; High vs. Low income; Kruskall Wallis Chi-square: 5.2067, p=0.0225
| | | Celery | No relationship, Statistically non-significant; Celery (stalk) in grocery stores; High vs. Low income; Kruskall Wallis Chi-square: 0.2384, p=0.6254
| | | Corn | No relationship, Statistically non-significant; Corn (3 pc) in grocery stores; High vs. Low income; Kruskall Wallis Chi-square: 2.1, p=0.1473
| | | Cucumbers | No relationship, Statistically non-significant; Cucumber (pc) in grocery stores; High vs. Low income; Kruskall Wallis Chi-square: 0, p=1.0000
| | | Lettuce | No relationship, Statistically non-significant; Lettuce in grocery stores; High vs. Low income; Kruskall Wallis Chi-square: 1.1126, p=0.2915
| | | Peppers | No relationship, Statistically non-significant; Peppers (pc) in grocery stores; High vs. Low income; Kruskall Wallis Chi-square: 0.7445, p=0.3882
| | | Tomatoes | No relationship, Statistically non-significant; Tomatoes (1 lb) in grocery stores; High vs. Low income; Kruskall Wallis Chi-square: 0.5038, p=0.4778
Davis, 2005 ^14^ | N=43000; Analytic N = about 43,000 households from 24 cities in 17 States; California (San Francisco/Oakland, Los Angeles, Visalia), Colorado (Denver, Grand Junction), Florida (Tampa/St. Petersburg), Georgia (Atlanta, Rome); Illinois (Chicago), Iowa (Cedar Rapids) | Income; - Low income; WIC eligible; - High income | Beans | No relationship, Statistically non-significant; Prices for dried beans/peas did not differ between income classes. (Statistical test NR)
| | | Breakfast cereals | No relationship, Statistically non-significant; Prices for baby cereals and ready-to-eat breakfast cereals did not differ between income classes. (Statistical test NR)
| | | Cheese | No relationship, Statistically non-significant; Prices for cheese did not differ between income classes. (Statistical test NR)
| | | Eggs | No relationship, Statistically non-significant; Prices for eggs did not differ between income classes. (Statistical test NR)
| | | Juice | No relationship, Statistically non-significant; Prices for fruit and vegetable juice did not differ between income classes. (Statistical test NR)
| | | Milk | No relationship, Statistically non-significant; Mean milk price (1 gal), Statistical test NR; Low income, WIC eligible, High income, p=non-significant; CA: $2.61, $2.57, $2.70; CO: $2.49, $2.52, $2.43; FL: $2.98, $3.00, $3.00; GA: $2.55, $2.61, $2.69; IA: $2.33, $2.36, $2.30; IL: $2.52, $2.46, $2.54; KS: $2.66, $2.64, $2.64; MA: $2.62, $2.65, $2.61; MI: $2.57, $2.55, $2.57; MN: $2.89, $2.88, $2.88; MO: $2.76, $2.77, $2.76; NY: $2.92, $2.87, $2.90; PA: $2.36, $2.48, $2.37; TN: $2.82, $2.81, $2.85; TX: $2.43, $2.37, $2.40; WA: $2.52, $2.52, $2.62; WI: $2.51, $2.53, $2.51
| | | Peanut butter | No relationship, Statistically non-significant; Prices for peanut butter did not differ between income classes. (Statistical test NR)
DeWeese, 2017 ^15^ | N=104; Analytic N is New Jersey corner stores for metro areas of Camden, Newark, New Brunswick, and Trenton, NJ | Income; - Low; - Med; - High | Chips | No relationship, Statistically non-significant; Mean price of chips, ANOVA, P=NS; Lowest income (≥54%): $0.45; Medium income (34-<54%): $0.49; Highest income (<34%): $0.45
| | | Fruit | No relationship, Statistically non-significant; Mean price of fruit, ANOVA, P=NS; Lowest income (≥54%): $0.49; Medium income (34-<54%): $0.50; Highest income (<34%): $0.47
Dunn, 2011 ^16^ | N=23; Analytic N = 23 stores from 6 rural counties in the Brazos Valley, located between Dallas and Houston.; Census block group characteristics of the included stores, Mean (SD): Median family income: $30,083 ($7,290); Proportion Black: 21.2% (16.1%); Proportion Hispanic: 16.5% (9.7%) | Income; Median family income | Fruit | Direct relationship (High variety), Statistically non-significant; No relationship (Basic variety), Statistically non-significant; Fruit Price Index--High Variety; Multivariate regression, R^2=0.19, N=21; Coefficient estimates (robust SE), adjusted for race; Median family income (ln): B=10.15 (5.99), p>0.05; Fruit Price Index--Basic Variety; Multivariate regression, R^2=0.02, N=22; Coefficient estimates (robust SE), adjusted for race; Median family income (ln): B=−0.12 (3.49), p>0.05
| | | Vegetables | Direct relationship, Statistically non-significant; Vegetable Price Index--High Variety; Multivariate regression, R^2=0.14, N=23; Coefficient estimates (robust SE), adjusted for race; Median family income (ln): B=13.87 (6.94), p>0.05; Vegetable Price Index--Basic Variety; Multivariate regression, R^2=0.15, N=23; Coefficient estimates (robust SE), adjusted for race; Median family income (ln): B=16.12 (8.11), p>0.05
| | | Apples | No relationship, Statistically non-significant; Price of apples ($/lb); Multivariate regression, R^2=0.09, N=21; Coefficient estimates (robust SE), adjusted for race; Median family income (ln): B=0.50 (0.45), p>0.05
| | | Avocados | Direct relationship, Statistically significant; Price of avocados ($/lb); Multivariate regression, R^2=0.48, N=21; Coefficient estimates (robust SE), adjusted for race; Median family income (ln): B=3.78 (1.37), p<0.01
| | | Bananas | No relationship, Statistically non-significant; Price of bananas ($/lb); Multivariate regression, R^2=0.17, N=21; Coefficient estimates (robust SE), adjusted for race; Median family income (ln): B=−0.16 (0.10), p>0.05
| | | Beans | Inverse relationship, Statistically significant; Price of green beans ($/lb); Multivariate regression, R^2=0.22, N=23; Coefficient estimates (robust SE), adjusted for race; Median family income (ln): B=−2.05 (1.03), p<0.05
| | | Berries | No relationship, Statistically non-significant; Price of berries ($/lb); Multivariate regression, R^2=0.11, N=21; Coefficient estimates (robust SE), adjusted for race; Median family income (ln): B=0.21 (1.04), p>0.05
| | | Carrots | No relationship, Statistically non-significant; Price of carrots ($/lb); Multivariate regression, R^2=0.15, N=23; Coefficient estimates (robust SE), adjusted for race; Median family income (ln): B=−0.16 (0.44), p>0.05
| | | Corn | No relationship, Statistically non-significant; Price of corn ($/lb); Multivariate regression, R^2=0.16, N=23; Coefficient estimates (robust SE), adjusted for race; Median family income (ln): B=0.03 (0.53), p>0.05
| | | Cruciferous vegetables | No relationship, Statistically non-significant; Price of cruciferous vegetables ($/lb); Multivariate regression, R^2=0.15, N=23; Coefficient estimates (robust SE), adjusted for race; Median family income (ln): B=0.26 (0.30), p>0.05
| | | Grapes | No relationship, Statistically non-significant; Price of grapes ($/lb); Multivariate regression, R^2=0.04, N=21; Coefficient estimates (robust SE), adjusted for race; Median family income (ln): B=0.54 (0.60), p>0.05
| | | Greens | No relationship, Statistically non-significant; Price of greens ($/lb); Multivariate regression, R^2=0.11, N=23; Coefficient estimates (robust SE), adjusted for race; Median family income (ln): B=−0.30 (0.33)
| | | Lettuce | No relationship, Statistically non-significant; Price of lettuce ($/lb); Multivariate regression, R^2=0.31, N=23; Coefficient estimates (robust SE), adjusted for race; Median family income (ln): B=1.11 (0.67), p>0.05
| | | Melons | No relationship, Statistically non-significant; Price of melons ($/lb); Multivariate regression, R^2=0.01, N=21; Coefficient estimates (robust SE), adjusted for race; Median family income (ln): B=0.09 (0.38), p>0.05
| | | Onions | No relationship, Statistically non-significant; Price of onions ($/lb); Multivariate regression, R^2=0.06, N=23; Coefficient estimates (robust SE), adjusted for race; Median family income (ln): B=0.51 (0.54), p>0.05
| | | Oranges | No relationship, Statistically non-significant; Price of oranges ($/lb); Multivariate regression, R^2=0.02, N=21; Coefficient estimates (robust SE), adjusted for race; Median family income (ln): B=−0.03 (0.40), p>0.05
| | | Peaches | No relationship, Statistically non-significant; Price of peaches ($/lb); Multivariate regression, R^2=0.08, N=21; Coefficient estimates (robust SE), adjusted for race; Median family income (ln): B=−0.30 (0.49), p>0.05
| | | Pears | No relationship, Statistically non-significant; Price of pears ($/lb); Multivariate regression, R^2=0.02, N=21; Coefficient estimates (robust SE), adjusted for race; Median family income (ln): B=−0.06 (0.55), p>0.05
| | | Potatoes | No relationship, Statistically non-significant; Price of potatoes ($/lb); Multivariate regression, R^2=0.13, N=23; Coefficient estimates (robust SE), adjusted for race; Median family income (ln): B=0.48 (0.39), p>0.05
| | | Squash | Direct relationship, Statistically significant; Price of squash ($/lb); Multivariate regression, R^2=0.26, N=23; Coefficient estimates (robust SE), adjusted for race; Median family income (ln): B=1.08 (0.41), p<0.01
| | | Tomatoes | No relationship, Statistically non-significant; Price of tomatoes ($/lb); Multivariate regression, R^2=0.07, N=23; Coefficient estimates (robust SE), adjusted for race; Median family income (ln): B=0.62 (0.49), p>0.05
French, 2010 ^17^ | N=90; Analytic N is households; Mean of four people per household.; Primary shoppers were 93% female; 78% White; Mean age 40.8 y (SD=7.3); 64% married or living with significant other; 25.8% had more than a college degree; mean BMI: 29.7 (SD=7.2) | Income; - Low; - Med; - High | Fruits and Vegetables | Direct relationship, Statistically significant; Monthly median price per person per ounce of fruits/vegetables eaten at home, Jonckheere-Terpstra test, p=0.007; Low: $0.08; Med: $0.08; High: $0.10
Gillespie, 2015 ^18^ | N=60; Analytic N = full-service grocery stores across 9 parishes; Median HH income: $45,392; African American population: 39% | Income | Healthier Market Basket | No relationship, Statistically non-significant; Price(Ln) of Nutrient-dense foods; Regression (adjusted for Black, real estate value, urban, chain, supercenter, services, store size, competition), N=50, R^2^: 0.184, Prob>F: 0.070; Coefficient (SE); Income(Ln): 0.143 (0.138), p>0.10
| | | Unhealthy food price | Direct relationship, Statistically significant; Price(Ln) of Energy-dense foods,; Regression (adjusted for Black, real estate value, urban, chain, supercenter, services, store size, competition), N=40, R^2^: 0.596, Prob>F: 0.000; Coefficient (SE); Income(Ln): −0.237 (0.131), p≤0.10; [10% increase in income was associated with a 2.37% decrease in price of energy-dense foods]
| | | Healthy to unhealthy ratio | Direct relationship (bread:cakes, potatoes:cakes, oatmeal:cakes, oatmeal:cola); Inverse relationship (milk:cola, bananas:cola, bananas:chips); Income was significant (p≤0.10) for 7 (26%) of the 45 regressions for nutrient-dense/energy-dense pricing ratios.; Models adjusted for Black, High or Low real estate value, urban, chain, supercenter, services, store size, and competition.; 4 regressions (15%) indicated that higher income resulted in relatively higher prices for nutrient-dense foods relative to energy-dense foods: whole-wheat bread, potatoes, and oatmeal, all relative to snack cakes, and oatmeal relative to cola.; 3 regressions (11%) indicated that higher income resulted in relatively lower prices for nutrient-dense foods relative to energy-dense foods: skim milk and bananas relative to cola and bananas relative to potato chips.; When the nutrient-dense market basket /energy-dense market basket cost ratio was analyzed, income was non-significant.
| | | Bananas | No relationship, Statistically non-significant; Price(Ln) of bananas (1 lb); Regression (adjusted for Black, real estate value, urban, chain, supercenter, services, store size, competition), N=59, R^2^: 0.128, Prob>F: 0.008; Coefficient (SE); Income(Ln): −0.212 (0.237), p>0.10
| | | Bread | No relationship, Statistically non-significant; Price(Ln) of whole wheat bread (20 oz); Regression (adjusted for Black, real estate value, urban, chain, supercenter, services, store size, competition), N=58, R^2^: 0.220, Prob>F: 0.036; Coefficient (SE); Income(Ln): 0.167 (0.257), p>0.10
| | | Broccoli | No relationship, Statistically non-significant; Price(Ln) of broccoli (1 lb); Regression (adjusted for Black, real estate value, urban, chain, supercenter, services, store size, competition), N=59, R^2^: 0.424, Prob>F: 0.000; Coefficient (SE); Income(Ln): 0.207 (0.185), p>0.10
| | | Chips | Direct relationship, Statistically significant; Price(Ln) of potato chips (12 oz); Regression (adjusted for Black, real estate value, urban, chain, supercenter, services, store size, competition), N=57, R^2^: 0.486, Prob>F: 0.000; Coefficient (SE); Income(Ln): 0.543 (0.215), p<0.05; [10% increase in income was associated with a 5.43% increase in price of potato chips]
| | | Ice cream | No relationship, Statistically non-significant; Price(Ln) of ice cream (0.5 gal); Regression (adjusted for Black, real estate value, urban, chain, supercenter, services, store size, competition), N=59, R^2^: 0.217, Prob>F: 0.018; Coefficient (SE); Income(Ln): 0.121 (0.186), p>0.10
| | | Milk | No relationship, Statistically non-significant; Price(Ln) of skim milk (1 gal); Regression (adjusted for Black, real estate value, urban, chain, supercenter, services, store size, competition), N=59, R^2^: 0.326, Prob>F: 0.001; Coefficient (SE); Income(Ln): 0.117 (0.087), p>0.10
| | | Oatmeal | No relationship, Statistically non-significant; Price(Ln) of oatmeal (18 oz); Regression (adjusted for Black, real estate value, urban, chain, supercenter, services, store size, competition), N=58, R^2^: 0.206, Prob>F: 0.006; Coefficient (SE); Income(Ln): 0.401 (0.307), p>0.10
| | | Oranges | No relationship, Statistically non-significant; Price(Ln) of oranges (1 lb); Regression (adjusted for Black, real estate value, urban, chain, supercenter, services, store size, competition), N=58, R^2^: 0.358, Prob>F: 0.000; Coefficient (SE); Income(Ln): 0.225 (0.204), p>0.10
| | | Soda | No relationship, Statistically non-significant; Price(Ln) of cola (2 L); Regression (adjusted for Black, real estate value, urban, chain, supercenter, services, store size, competition), N=58, R^2^: 0.488, Prob>F: 0.000; Coefficient (SE); Income(Ln): 0.082 (0.225), p>0.10
Gosliner, 2018 ^19^ | N=1474; Analytic N=1474 stores in 470 unique; census tracts within 225 low-income neighborhoods in cities and towns across 44 California counties. | Geographic location; - Low-income neighborhoods; - County average | Apples | Inverse relationship, Statistically significant; Average lowest price of apples ($/lb) by store type; Mean (SD, range), Relative price difference from county chain supermarket average, Statistical test NR; Large groceries (n=218): $1.17 (0.39, 0.66-2.99), 44%; Small markets (n=312): $1.18 (0.37, 0.63-2.59), 53%; Convenience stores (n=130): $1.58 (0.50, 0.69-2.80), 110%
| | | Bananas | Inverse relationship, Statistically significant; Average lowest price of bananas ($/lb) by store type; Mean (SD, range), Relative price difference from county chain supermarket average, Statistical test NR; Large groceries (n=218): $0.70 (0.16, 0.49-1.49), 15%; Small markets (n=336): $0.85 (0.31, 0.49-2.19), 39%; Convenience stores (n=150): $1.30 (0.46, 0.49-2.19), 115%
| | | Broccoli | No relationship, Statistically non-significant; Average lowest price of broccoli ($/lb) by store type; Mean (SD, range), Relative price difference from county chain supermarket average, Statistical test NR; Large groceries (n=199): $1.30 (0.49, 0.68-3.19), 1%; Small markets (n=142): $1.33 (0.56, 0.68-3.18), 6%; Convenience stores: Available in too few stores for inclusion
| | | Cabbage | No relationship, Statistically non-significant; Average lowest price of cabbage ($/lb) by store type; Mean (SD, range), Relative price difference from county chain supermarket average, Statistical test NR; Large groceries (n=172): $0.74 (0.27, 0.38-1.59) 0%; Small markets (n=261): $0.66 (0.26, 0.34-1.50), −1%; Convenience stores: Available in too few stores for inclusion
| | | Carrots | Inverse relationship, Statistically significant; Average lowest price of carrots ($/lb) by store type; Mean (SD, range), Relative price difference from county chain supermarket average, Statistical test NR; Large groceries (n=179): $0.84 (0.33, 0.50-2.14), 33%; Small markets (n=242): $0.91 (0.37, 0.50-2.20), 43%; Convenience stores (n=24): $1.22 (0.58, 0.50-2.00), 102%
| | | Oranges | Inverse relationship, Statistically significant; Average lowest price of oranges ($/lb) by store type; Mean (SD, range), Relative price difference from county chain supermarket average, Statistical test NR; Large groceries (n=200): $0.95 (0.40, 0.48-1.49), 35%; Small markets (n=249): $0.88 (0.41, 0.47-2.20), 27%; Convenience stores (n=88): $1.36 (0.59, 0.50-2.20), 107%
| | | Tomatoes | Inverse relationship, Statistically significant; Average lowest price of tomatoes ($/lb) by store type; Mean (SD, range), Relative price difference from county chain supermarket average, Statistical test NR; Large groceries (n=197): $1.21 (0.45, 0.59-2.66), 13%; Small markets (n=311): $1.12 (0.41, 0.59-2.79), 6%; Convenience stores (n=57): $1.21 (0.38, 0.69-2.19), 23%
Hardin-Fanning, 2015 ^20^ | N=4; Analytic N is number of counties 4 counties compared with 1 store/county; All groceries were regional or national chain stores of similar size and food product variety | Geographic location; - FD-HP; - U-MP; - U-LP; - HP | USDA Market Basket | Inverse relationship (healthier foods), Statistically significant; Mean price/serving, repeated measures ANOVA; (adjusted for month and ONQI score (fixed effects) and food item identifier (random effect)); County: F(3,1365) = 22.9, p<0.0001; County × Month: p=0.4; Mean price/serving, repeated measures ANOVA; (adjusted for month and quartile × month (fixed effects) and food item identifier (random effect)); County: F(3,1347) = 24.5, p<0.0001; County × Month: p>0.0005; ONQI quartile × County: F(9,1347) = 6.7, p<0.0001; Mean price/serving, Post-hoc analysis; FD-HP (lower per capita income): $0.40 vs. U-MP and U-LP, p<0.0001; vs. HP, p=0.0002; U-MP and U-LP (higher per capita income; average): $0.36; HP (higher per capita income): $0.38 vs. U-LP p=0.003
Hardin-Fanning, 2017 ^21^ | N=15; Analytic N is number of counties 15 counties compared with 1 store/county; All groceries were regional or national chain stores of similar size and food product variety | Geographic location; - Least healthy counties (highest average poverty rates); - Moderately healthy counties (lower average poverty rates); - Most healthy counties (lower average poverty rates) | USDA Market Basket | Inverse relationship, Statistically significant; GEE Model, Price per serving across health ranking groups, adjusted for ONQI quartile, county population, Appalachian status, and multiple measurements per county.; Chi-squared: 12, P=0.003; Post-hoc analysis of pairwise differences, mean price/serving:; Least healthy (highest poverty) $0.58; Moderately healthy (lower poverty) $0.53; Most healthy (lower poverty) $0.50; Relative price per serving ($) by health tertiles:; Least healthy (highest poverty) vs. Most healthy (lower poverty): B = 0.08, SE = 0.02, Z=3.8, P<0.001; Least healthy (highest poverty) vs. Moderately healthy (lower poverty): B = 0.05, SE = 0.02, Z=2.3, P=0.024; Moderately healthy vs. Most healthy, P=NS
Hatzenbuehler, 2012 ^22^ | N=59; Analytic N is supermarkets in Baton Rouge, Louisiana, metropolitan area; Mean income: $40,704 (range: $17,170-77,668); Mean household size: 2.61 (range: 1.87-3.08); Mean % Black: 32.53% (0.50-97.00%); Mean % other minority: 4.55% (1.06-11.96%) | Income; continuous | TFP Food Basket | No relationship, Statistically non-significant; TFP market basket, Ordinary least squares; Income: B: 0.29, t-value: 0.76, p>0.05; R^2^: 0.3250, Model F-value: 4.10, p<0.01; Adjusted for population density, household size, chain, supercenter, services, store size, Black, other minority
| | | 2005 DGA Market Basket | No relationship, Statistically non-significant; Stewart DGA market basket, Ordinary least squares; Income: B: 0.52, t-value: 1.50, p>0.05; R^2^: 0.3655, Model F-value: 4.71, p<0.01; Adjusted for population density, household size, chain, supercenter, services, store size, Black, other minority
| | | Dairy | Direct relationship (2005 DGA), Statistically significant; No relationship (TFP), Statistically non-significant; Low-fat dairy products for the Stewart 2005 DGA market basket; Ordinary least squares; Income: B: 0.17, t-value: 2.19, p<0.05; R^2^: 0.2407, Model F-value: 3.04, p<0.01; Adjusted for population density, household size, chain, supercenter, services, store size, Black, other minority; Low-fat dairy products for the TFP market basket; Ordinary least squares; Income: B: 0.06, t-value: 1.43, p>0.05; R^2^: 0.1491, Model F-value: 2.13, p<0.05; Adjusted for population density, household size, chain, supercenter, services, store size, Black, other minority
| | | Fruit | Direct relationship (2005 DGA), Statistically significant; No relationship (TFP), Statistically non-significant; Fruit for the Stewart 2005 DGA market basket; Ordinary least squares; Income: B: 0.13, t-value: 2.55, p<0.05; R^2^: 0.3778, Model F-value: 4.91, p<0.01; Adjusted for population density, household size, chain, supercenter, services, store size, Black, other minority; Fruit for the TFP market basket; Ordinary least squares; Income: B: 0.23, t-value: 1.52, p>0.05; R^2^: 0.2893, Model F-value: 3.62, p<0.01; Adjusted for population density, household size, chain, supercenter, services, store size, Black, other minority
| | | Greens | No relationship, Statistically non-significant; Dark green vegetables for the Stewart 2005 DGA market basket; Ordinary least squares; Income: B: 0.02, t-value: 1.00, p>0.05; R^2^: 0.1433, Model F-value: 2.08, p<0.05; Adjusted for population density, household size, chain, supercenter, services, store size, Black, other minority; Dark green vegetables for the TFP market basket; Ordinary least squares; Income: B: 0.00, t-value: 0.87, p>0.05; R^2^: 0.1135, Model F-value: 1.83, p>0.05; Adjusted for population density, household size, chain, supercenter, services, store size, Black, other minority
| | | Whole grains | No relationship, Statistically non-significant; Whole grains for the Stewart 2005 DGA market basket; Ordinary least squares; Income: B: −0.01, t-value: −0.17, p>0.05; R^2^: 0.1784, Model F-value: 2.40, p<0.05; Adjusted for population density, household size, chain, supercenter, services, store size, Black, other minority; Whole grains for the TFP market basket; Ordinary least squares; Income: B: 0.00, t-value: 0.35, p>0.05; R^2^: 0.1524, Model F-value: 2.16, p<0.05; Adjusted for population density, household size, chain, supercenter, services, store size, Black, other minority
Hayes, 2000 ^23^ | N=57; Analytic N is supermarkets identified by the Food and Safety Inspection Report:; Poor: n=21 stores, 10 zip codes; Middle: n=14 stores, 7 zip codes; Upper: n=22 stores, 11 zip codes; NYC consists of New York, Bronx, Kings, Queens, Richmond, and Westchester co | Income; - Poor; - Middle; - Upper | Market basket | Direct relationship, Statistically non-significant; Mean (SE) total cost in logarithms of market basket, weighted by expenditure-shares, Mean difference; Poor: 3.955 (0.008) or $52.20; Middle: 3.968 (0.013) or $52.88; Upper: 3.971 (0.014) or $53.04; Poor-upper difference: −0.016 (0.016) or −$0.84; P=NS; Mean (SE) total cost of market basket in logarithms, unweighted; Poor: 3.925 (0.008) or $50.65; Middle: 3.938 (0.014) or $51.32; Upper: 3.942 (0.015) or $51.52; Poor-upper difference: −0.016 (0.017) or −$0.87; P=NS
| | | Apples | Direct relationship, Statistically significant; Mean (SE) price in logarithms of Apples, Mean difference; Poor: −0.120 (0.032) or $0.89; Middle: 0.058 (0.032) or $1.06; Upper: 0.082 (0.028) or $1.09; Poor-upper difference: −0.202 (0.043) or −$0.20; Significantly different
| | | Bananas | Direct relationship, Statistically significant; Mean (SE) price in logarithms of Bananas, Mean difference; Poor: −0.799 (0.038) or $0.45; Middle: −0.854 (0.067) or $0.43; Upper: −0.636 (0.049) or $0.53; Poor-upper difference: −0.163 (0.062) or $0.08; Significantly different
| | | Bread | Direct relationship, Statistically non-significant; Mean (SE) price in logarithms of Bread, Mean difference; Poor: 0.468 (0.023) or $1.60; Middle: 0.538 (0.12) or $1.71; Upper: 0.504 (0.014) or $1.66; Poor-upper difference: −0.036 (0.027) or −$0.06; P=NS
| | | Breakfast cereals | Inverse relationship, Statistically significant; Mean (SE) price in logarithms of Cereal, Mean difference; Poor: 0.927 (0.005) or $2.53; Middle: 0.926 (0.016) or $2.52; Upper: 0.876 (0.009) or $2.40; Poor-upper difference: 0.052 (0.010) or $0.13; Significantly different
| | | Butter | Inverse relationship, Statistically non-significant; Mean (SE) price in logarithms of Butter, Mean difference; Poor: 1.106 (0.009) or $3.02; Middle: 1.060 (0.030) or $2.89; Upper: 1.068 (0.027) or $2.91; Poor-upper difference: 0.037 (0.028) or $0.11; P=NS
| | | Cheese | Inverse relationship, Statistically non-significant; Mean (SE) price in logarithms of Cheese, Mean difference; Poor: 1.180 (0.21) or $3.25; Middle: 1.166 (0.046) or $3.21; Upper: 1.152 (0.027) or $3.16; Poor-upper difference: 0.028 (0.034) or $0.09; P=NS
| | | Chicken | Direct relationship, Statistically non-significant; Mean price in logarithms of Chicken, Mean difference; Poor: 0.788 (0.044) or $2.20; Middle: 0.755 (0.069) or $2.13; Upper: 0.862 (0.052) or $2.37; Poor-upper difference: −0.074 (0.068) or −$0.17; P=NS
| | | Cooking oil | No relationship, Statistically non-significant; Mean (SE) price in logarithms of Oil, Mean difference; Poor: 0.533 (0.005) or $1.70; Middle: 0.570 (0.017) or $1.77; Upper: 0.542 (0.009) or $1.72; Poor-upper difference: −0.009 (0.011) or $0.02; P=NS
| | | Eggs | Direct relationship, Statistically non-significant; Mean (SE) price in logarithms of Eggs, Mean difference; Poor: 0.192 (0.020) or $1.21; Middle: 0.222 (0.035) or $1.25; Upper: 0.285 (0.039) or $1.33; Poor-upper difference: −0.074 (0.044) or −$0.12; P=NS
| | | Flour | Direct relationship, Statistically non-significant; Mean (SE) price in logarithms of Flour, Mean difference; Poor: 0.648 (0.046) or $1.91; Middle: 0.700 (0.024) or $2.01; Upper: 0.676 (0.026) or $1.97; Poor-upper difference: −0.029 (0.052) or −$0.06; P=NS
| | | Ground beef | Direct relationship, Statistically non-significant; Mean (SE) price in logarithms of Ground beef, Mean difference; Poor: 1.444 (0.042) or $4.24; Middle: 1.490 (0.077) or $4.44; Upper: 1.530 (0.044) or $4.62; Poor-upper difference: −0.086 (0.061) or $0.38; P=NS
| | | Juice | Direct relationship, Statistically significant; Mean (SE) price in logarithms of Orange Juice, Mean difference; Poor: 0.919 (0.026) or $2.51; Middle: 0.915 (0.031) or $2.50; Upper: 1.011 (0.022) or $2.75; Poor-upper difference: −0.092 (0.034) or −$0.24; Significantly different
| | | Milk | No relationship, Statistically non-significant; Mean (SE) price in logarithms of Milk, Mean difference; Poor: 0.932 (0.008) or $2.54; Middle: 0.885 (0.029) or $2.42; Upper: 0.948 (0.020) or $2.58; Poor-upper difference: −0.015 (0.022) or −$0.04; P=NS
| | | Pasta | No relationship, Statistically non-significant; Mean (SE) price in logarithms of Spaghetti, Mean difference; Poor: −0.025 (0.044) or $0.98; Middle: 0.071 (0.039) or $1.07; Upper: 0.002 (0.032) or $1.00; Poor-upper difference: −0.027 (0.054) or $0.02; P=NS
| | | Rice | No relationship, Statistically non-significant; Mean (SE) price in logarithms of Long-Grain Rice, Mean difference; Poor: 1.104 (0.017) or $3.02; Middle: 1.116 (0.013) or $3.05; Upper: 1.088 (0.018) or $2.97; Poor-upper difference: 0.016 (0.025) or $0.05; P=NS
| | | Sugar | Direct relationship, Statistically non-significant; Mean (SE) price in logarithms of Sugar, Mean difference; Poor: 0.957 (0.008) or $2.60; Middle: 0.895 (0.025) or $2.45; Upper: 0.990 (0.019) or $2.69; Poor-upper difference: −0.033 (0.020) or −$0.09; P=NS
| | | Tuna | No relationship, Statistically non-significant; Mean (SE) price in logarithms of Tuna, Mean difference; Poor: −0.059 (0.026) or $0.94; Middle: 0.034 (0.058) or $1.03; Upper: −0.051 (0.031) or $0.95; Poor-upper difference: −0.008 (0.040) or $0.01; P=NS
Jetter, 2006 ^24^ | N=25; Analytic N = stores; 12 stores in Los Angeles; 13 stores in Sacramento | Income; Continuous and low vs. higher | TFP Food Basket | Direct relationship (continuous), Statistically significant; No relationship (lower vs. higher), Statistically non-significant; Cost of a market basket (either TFP or Healthier); Regression model (adjusted for: store type, fiber (ln), fat (ln), store density, store access); Coefficient; Low-income area: −0.001, p>0.1; Income (ln; continuous): 0.079, p<0.05
Jewell, 2019 ^25^ | N=21; Analytic N is neighborhoods.; Stores: N=108 from 710 census tracts | Geographic location; - CX3; - Adjacent | Fruits and Vegetables | Direct relationship, Statistically non-significant; Median (IQR) produce price, Kruskal-Wallis, p=0.06; CX3 neighborhoods: $1.05 (0.63); Adjacent neighborhoods: $1.50 (0.97)
Kern, 2016 ^26^ | N=1743; Analytic N is stores (large chain supermarkets and superstores) across 41 states and 1694 census blocks. | SES proxy; Neighborhood SES index | Milk | Direct relationship, Statistically significant; Hierarchical model of price of milk ($/12 fl. oz) per neighborhood SES z-score; Estimate (95% CI); Adjusted (race, age, region, urbanicity, supermarket density, toilet paper price, soda price, county and state): 0.0149 (0.0104, 0.0193), p<0.0001; Bivariate regression model of price of milk ($/12 fl. oz) per neighborhood SES z-score, p<0.0001; Mean (SD); Lowest SES tertile (least advantaged, n=581): $0.60 (0.11); Middle SES tertile (n=582): $0.61 (0.11); Highest SES tertile (most advantaged, n=580): $0.65 (0.10)
| | | Soda | Direct relationship, Statistically significant; Hierarchical model of price of soda ($/12 fl. oz) per neighborhood SES z-score; Estimate (95% CI); Adjusted (race, age, region, urbanicity, supermarket density, toilet paper price, milk price, county and state): 0.0024 (0.0012, 0.0035), p<0.0001; Bivariate regression model of price of soda ($/12 fl. oz) per neighborhood SES z-score, p<0.0001; Mean (SD); Lowest SES tertile (least advantaged, n=581): $0.23 (0.02); Middle SES tertile (n=582): $0.22 (0.02); Highest SES tertile (most advantaged, n=580): $0.23 (0.02)
Kern, 2017 ^27^ | N=1953; Analytic N is stores | SES proxy; Neighborhood SES index | Healthy food price | Direct relationship (unadjusted), Statistically significant; Estimate (95%): Unadjusted (county and state): 0.00452 (0.0034, 0.0056), p<0.0001; Partially adjusted (age, region, urbanicity, population density, supermarket density, toilet paper price, county and state): 0.00085 (−0.00027, 0.00198), p=0.1370; Fully adjusted (age, region, urbanicity, population density, supermarket density, toilet paper price, race, county and state): 0.00090 (−0.0007, 0.0025), p= 0.2836;; Price of food by Neighborhood SES quintile, mean (SD):; Lowest quintile (least advantaged): $0.581 (0.047); Second quintile: $0.581 (0.048); Middle quintile: $0.589 (0.053); Fourth quintile: $0.590 (0.057); Highest quintile (most advantaged): $0.611 (0.068)
| | | Unhealthy food price | Direct relationship (unadjusted), Statistically significant; Inverse relationship (partially adjusted), Statistically significant; Estimate (95% CI); Unadjusted (county and state): 0.00057 (0.0001, 0.0011), p=0.0234; Partially adjusted (age, region, urbanicity, population density, supermarket density, toilet paper price, county and state): −0.00102 (−0.00148, −0.00056), p<0.0001; Fully adjusted (age, region, urbanicity, population density, supermarket density, toilet paper price, race, county and state): 0.00055 (−0.0001, 0.0012), p=0.1110; Price of food by Neighborhood SES quintile, mean (SD):; Lowest quintile (least advantaged): $0.299 (0.019); Second quintile: $0.295 (0.020); Middle quintile: $0.295 (0.017); Fourth quintile: $0.294 (0.016); Highest quintile (most advantaged): $0.306 ($0.039)
| | | Dairy | Inverse relationship, Statistically significant; Estimate (95% CI); Unadjusted (county and state): −0.01323 (−0.0153, −0.0112), p<0.0001; Fully adjusted (age, region, urbanicity, population density, supermarket density, toilet paper price, race, county and state): −0.01836 (−0.0215, −0.0152), p<0.0001
| | | Fruit Juice and Frozen Vegetables | Direct relationship, Statistically significant; Estimate (95% CI); Unadjusted (county and state): 0.01386 (0.0126, 0.0151), p<0.0001; Fully adjusted (age, region, urbanicity, population density, supermarket density, toilet paper price, and race, county and state): 0.01096 (0.0091, 0.0128), p<0.0001
| | | Salty Snacks | Inverse relationship, Statistically significant; Estimate (95% CI); Unadjusted (county and state): −0.00216 (−0.0025, −0.0018), p<0.0001; Fully adjusted (age, region, urbanicity, population density, supermarket density, toilet paper price, race, county and state): −0.00125 (−0.0018 −0.0007), p<0.0001
| | | Soda | No relationship, Statistically non-significant; Estimate (95% CI); Unadjusted (county and state): 0.00051 (−0.0001, 0.0011), p=0.0937; Fully adjusted (age, region, urbanicity, population density, supermarket density, toilet paper price, either race, county and state): 0.00065 (−0.0003, 0.0016), p=0.1682
| | | Sweets | Direct relationship, Statistically significant; Estimate (95% CI); Unadjusted (county and state): 0.00267 (0.0018, 0.0035), p<0.0001; Fully adjusted (age, region, urbanicity, population density, supermarket density, toilet paper price, race, county and state): 0.00153 (0.0005, 0.0026), p=0.0054
Leider, 2019 ^28^ | N=11767; Analytic N is product-level observations from 581 stores | Income; Continuous (units of $10k) | Energy drinks | No relationship, Statistically non-significant; Energy drinks (n=2,276); Beta coefficient (95% CI), Multiple linear regression; Median HH income (units of $10k): 0.02 (−0.05, 0.10), p>0.05; % population <125% poverty level: 0.02 (−0.00, 0.04), p>0.05; Adjusted for beverage size, sale status, store type, race/ethnicity, site
| | | Juice | No relationship, Statistically non-significant; Juice drinks (non-100% juice, n=886); Beta coefficient (95% CI), Multiple linear regression; Median HH income (units of $10k): 0.02 (−0.03, 0.07), p>0.05; % population <125% poverty level: 0.00 (−0.01, 0.02), p>0.05; Adjusted for beverage size, sale status, store type, race/ethnicity, site
| | | Ready-to-drink tea and coffee | No relationship, Statistically non-significant; Ready-to-drink tea and coffee (n=1,454); Beta coefficient (95% CI), Multiple linear regression; Median HH income (units of $10k): 0.02 (−0.09, 0.12), p>0.05; % population <125% poverty level: −0.02 (−0.05, 0.00), p>0.05; Adjusted for beverage size, sale status, store type, race/ethnicity, site
| | | Soda | Direct relationship, Statistically significant; Soda (n=5,220); Beta coefficient (95% CI), Multivariable linear regression; Median HH income (units of $10k): 0.02 (0.00, 0.04), p<0.05; % population <125% poverty level: 0.00 (−0.01, 0.00), p>0.05; Adjusted for beverage size, sale status, store type, race/ethnicity, site
| | | Sports drinks | No relationship, Statistically non-significant; Sports drinks (n=1,931); Beta coefficient (95% CI), Multivariable linear regression; Median HH income (units of $10k): 0.00 (−0.03, 0.03), p>0.05; % population <125% poverty level: 0.00 (−0.00, 0.01), p>0.05; Adjusted for beverage size, sale status, store type, race/ethnicity, site
| | | Sugar-sweetened beverages | No relationship, Statistically non-significant; All sugar-sweetened beverages (N=11,767); Beta coefficient (95% CI), Multivariable linear regression; Median HH income (units of $10k): 0.02 (−0.01, 0.04), p>0.05; % population <125% poverty level: 0.00 (−0.01, 0.01), p>0.05; Adjusted for beverage category, beverage size, sale status, store type, race/ethnicity, site
Leone, 2011 ^29^ | N=73; Analytic N is stores; County population was 239,452.; Race: White 66.4%, Black 29.1%, other race 4.5%; 18.2% lived below poverty | Income; - Low; - High | Fruits and Vegetables | No relationship, Statistically non-significant; Neighborhood characteristics (including income) were not significantly related to the price of more healthful foods.
| | | Bread | No relationship, Statistically non-significant; Neighborhood characteristics (including income) were not significantly related to the price of whole-wheat bread.
| | | Milk | No relationship, Statistically non-significant; Neighborhood characteristics (including income) were not significantly related to the price of low-fat milk.
Lopez-Class, 2010 ^30^ | N=32; Analytic N is stores; Latino and surrounding neighborhoods in a city located in East Central New York, on the Mohawk River.; Population of ~18,000 with 16% Latino, of those 72% are Puerto-Rican. City is divided into four geographic areas: Cork Hill, South Side, the Projects, and East End | Geographic location; - Latino neighborhood; - Non-Latino neighborhood | Apples | Inverse relationship, Statistically significant; Apple, medium; Mean price (SD), range, t-test, p=0.038; Latino neighborhood: $0.39 (0.07), 0.30-0.49; Non-Latino neighborhood: $0.28 (0.08), 0.15-0.36
| | | Bread | Inverse relationship, Statistically significant; High-fiber bread (≥2g per slice), 24 oz; Mean price (SD), range, t-test, p=0.028; Latino neighborhood: $3.89 (only mean available); Non-Latino neighborhood: $2.72 (0.94), 1.44-3.84
| | | Cucumbers | Inverse relationship, Statistically significant; Cucumber, medium; Mean price (SD), range, t-test, p=0.041; Latino neighborhood: $0.54 (0.05), 0.49-0.59; Non-Latino neighborhood: $0.39 (0.09), 0.33-0.49
| | | Milk | No relationship, Statistically non-significant; Low-fat (≤1% milk), quart; Mean price (SD), range, t-test, p=0.081; Latino neighborhood: $1.08 (0.16), 0.95-1.29; Non-Latino neighborhood: $0.93 (0.09), 0.80-0.99; Low-fat (≤1% milk), half gallon; Mean price (SD), range, p=0.746; Latino neighborhood: $1.51 (0.19), 1.09-1.75; Non-Latino neighborhood: $1.54 (0.20), 1.29-1.99; Low-fat (≤1% milk), gallon; Mean price (SD), range, p=0.888; Latino neighborhood: $2.59 (0.40), 1.99-2.79; Non-Latino neighborhood: $2.62 (0.31), 2.25-2.99
| | | Oranges | Inverse relationship, Statistically non-significant; Orange, medium; Mean price (SD), range, t-test, p=0.267; Latino neighborhood: $0.54 (0.18), 0.33-0.75; Non-Latino neighborhood: $ 0.43 (0.09), 0.32-0.50
| | | Tomatoes | No relationship, Statistically non-significant; Tomato, medium; Mean price (SD), range, t-test, p=0.315; Latino neighborhood: $0.33 (0.11), 0.11-0.40; Non-Latino neighborhood: $0.51 (0.29), 0.24-0.99
Rimkus, 2015 ^31^ | N=8793; Analytic N = food stores across 468 communities spanning 46 states Communities observed were defined by school enrollment zones for students surveyed as part of the Monitoring the Future study and were nationally representative of where 8th, 10th, and 12th grade public school students reside. | Income; - High (ref); - Medium; - Low | Milk | Inverse relationship (various), Statistically significant; No relationship, Statistically non-significant; All stores; Ordinary least squares regression, adjusted for: US Census Division, year of data collection, store type, race, ethnicity, urbanicity; Beta coefficient (SE) of whole milk prices; High income: Reference; Medium income: 0.067 (0.043), p>0.05; Low income: 0.091 (0.042), p<0.05; Beta coefficient (SE) of 2% milk prices; High income: Reference; Medium income: 0.064 (0.041), p>0.05; Low income: 0.075 (0.041), p>0.05; Beta coefficient (SE) of 1% milk prices; High income: Reference; Medium income: −0.017 (0.046), p>0.05; Low income: −0.006 (0.055), p>0.05; Beta coefficient (SE) of skim milk prices; High income: Reference; Medium income: −0.008 (0.045), p>0.05; Low income: −0.0034 (0.047), p>0.05; Supermarkets; Ordinary least squares regression, adjusted for: US Census Division, year of data collection, race, ethnicity, urbanicity; Beta coefficient (SE) of whole milk prices; High income: Reference; Medium income: 0.091 (0.060), p>0.05; Low income: 0.069 (0.067), p>0.05; Beta coefficient (SE) of 2% milk prices; High income: Reference; Medium income: 0.067 (0.063), p>0.05; Low income: 0.032 (0.067), p>0.05; Beta coefficient (SE) of 1% milk prices; High income: Reference; Medium income: 0.084 (0.064), p>0.05; Low income: 0.036 (0.067), p>0.05; Beta coefficient (SE) of skim milk prices; High income: Reference; Medium income: 0.069 (0.068), p>0.05; Low income: 0.021 (0.070), p>0.05; Grocery stores; Ordinary least squares regression, adjusted for: US Census Division, year of data collection, race, ethnicity, urbanicity; Beta coefficient (SE) of whole milk prices; High income: Reference; Medium income: 0.058 (0.085), p>0.05; Low income: 0.117 (0.098), p>0.05; Beta coefficient (SE) of 2% milk prices; High income: Reference; Medium income: 0.073 (0.086), p>0.05; Low income: 0.122 (0.089), p>0.05; Beta coefficient (SE) of 1% milk prices; High income: Reference; Medium income: 0.217 (0.101), p<0.05; Low income: 0.212 (0.106), p<0.05; Beta coefficient (SE) of skim milk prices; High income: Reference; Medium income: 0.210 (0.108), p>0.05; Low income: 0.153 (0.111), p>0.05; Limited-service stores; Ordinary least squares regression, adjusted for: US Census Division, year of data collection, race, ethnicity, urbanicity; Beta coefficient (SE) of whole milk prices; High income: Reference; Medium income: 0.064 (0.045), p>0.05; Low income: 0.092 (0.041), p<0.05; Beta coefficient (SE) of 2% milk prices; High income: Reference; Medium income: 0.061 (0.044), p>0.05; Low income: 0.079 (0.043), p>0.05; Beta coefficient (SE) of 1% milk prices; High income: Reference; Medium income: −0.085 (0.051), p>0.05; Low income: −0.033 (0.064), p>0.05; Beta coefficient (SE) of skim milk prices; High income: Reference; Medium income: −0.060 (0.046), p>0.05; Low income: −0.075 (0.050), p>0.05
Smith, 2013 ^32^ | N=28; Analytic N = 28 convenience stores from 2 neighborhoods in Bexar County, TX.; ZIP A and ZIP B has the highest and lowest city-levels of adults clinically diagnosed with diabetes. | Geographic location; - Lower income; - Higher income | Apples | No relationship, Statistically non-significant; Price of apples; Mean (SD), t-test, p=0.818; ZIP A (lower income, n=5): $1.12 (0.94); ZIP B (higher income, n=5): $1.24 (0.53)
| | | Bananas | Direct relationship, Statistically significant; Price of bananas; Mean (SD), t-test, p=0.015; ZIP A (lower income, n=5): $0.43 (0.15); ZIP B (higher income, n=6): $1.13 (0.43)
| | | Bread | Direct relationship (White bread), Statistically significant; No relationship (Whole grain bread), Statistically non-significant; Price of whole grain bread; Mean (SD), t-test, p=0.203; ZIP A (lower income, n=3): $2.01 (0.77); ZIP B (higher income, n=7): $2.83 (0.17); Price of white bread; Mean (SD), t-test, p=0.001; ZIP A (n=15): $2.06 (0.39); ZIP B (n=8): $2.65 (0.32)
| | | Broccoli | Direct relationship, Statistically significant; Price of broccoli; Mean (SD), t-test, p<0.001; ZIP A (lower income, n=1): $0.07 (0.30); ZIP B (higher income, n=1): $2.99 (0.00)
| | | Chips | No relationship, Statistically non-significant; Price of baked potato chips; Mean (SD), t-test, p=NR; ZIP A (lower income, n=3): $0.99 (0.00); ZIP B (higher income, n=8): $0.99 (0.00); Price of regular potato chips; Mean (SD), t-test, p=0.868; ZIP A (n=18): $2.22 (1.43); ZIP B (n=9): $2.32 (1.58)
| | | Cucumbers | Direct relationship, Statistically significant; Price of cucumbers; Mean (SD), t-test, p<0.001; ZIP A (lower income, n=3): $0.14 (0.34); ZIP B (higher income, n=1): $2.99 (0.00)
| | | Juice | No relationship, Statistically non-significant; Price of 100% juice (no sugar added; 15.2 oz); Mean (SD), t-test, p=0.071; ZIP A (lower income, n=13): $1.66 (0.19); ZIP B (higher income, n=7): $2.00 (0.58); Price of juice drink (sugar added: 15.2 oz); Mean (SD), t-test, p=0.487; ZIP A (n=6): $1.55 (0.15); ZIP B (n=5): $1.63 (0.23)
| | | Melons | No relationship, Statistically non-significant; Price of watermelon; Mean (SD), t-test, p=0.873; ZIP A (lower income, n=2): $1.99 (0.00); ZIP B (higher income, n=5): $2.19 (1.09)
| | | Milk | No relationship, Statistically non-significant; Price of milk: low fat, skim, or 1% (half gallon); Mean (SD), t-test, p=0.130; ZIP A (lower income, n=2): $3.19 (0.28); ZIP B (higher income, n=1): $2.29 (0.42); Price of milk: 2% (half gallon); Mean (SD), t-test, p=0.852; ZIP A (n=5): $3.29 (0.27); ZIP B (n=8): $3.14 (1.30)
| | | Oranges | Direct relationship, Statistically significant; Price of oranges; Mean (SD), t-test, p=0.018; ZIP A (lower income, n=3): $0.45 (0.09); ZIP B (higher income, n=4): $0.90 (0.21)
| | | Soda | Direct relationship (diet cola), Statistically significant; No relationship (regular cola), Statistically non-significant; Price of diet cola (20 oz); Mean (SD), t-test, p=0.044; ZIP A (lower income, n=19): $1.35 (0.13); ZIP B (higher income, n=9): $1.45 (0.05); Price of regular cola (20 oz); Mean (SD), t-test, p=0.060; ZIP A (n=19): $1.37 (0.11); ZIP B (n=9): $1.45 (0.05)
| | | Tomatoes | Direct relationship, Statistically significant; Price of tomatoes; Mean (SD), t-test, p=0.010; ZIP A (lower income, n=7): $0.18 (0.27); ZIP B (higher income, n=1): $0.99 (0.00)
Stewart, 2011 ^33^ | N=7143; N is households who participated in the Nielsen-run panel for all 12 months of 2006; Nielsen provides a sample weight to be nationally representative; Mean household income: $27,000; Mean age: 54.9 y; Mean household size: 2.32 people; Black: 13%, Hispanic | Income; continuous | Salty Snacks | Direct relationship, Statistically significant; Salty snacks; Coefficient (SE), R^2=0.05; Household income: 0.005 (0.0015), p<0.01; Household income squared: −0.0003 (0.0002), p>0.1; Poverty principal component: 0.0005 (0.0004), p>0.1; Adjusted for household size, age, education, household includes child, homemaker in household, race/ethnicity, urbanicity, poverty, residential community, racial composition of community, geographic region (east, south, west)
| | | Vegetables | Direct relationship, Statistically significant; Fresh vegetables; Coefficient (SE), R^2=0.14; Household income: 0.0293 (0.0372), p<0.01; Household income squared: −0.0019 (0.0004), p<0.01; Poverty principal component: −0.0009 (0.0011), p>0.1; Adjusted for household size, age, education, household includes child, homemaker in household, race/ethnicity, urbanicity, poverty, residential community, racial composition of community, geographic region (east, south, west)
Talukdar, 2008 ^34^ | N=115; Analytic N = 115 stores from 17 of the 27 zip codes in of Buffalo city and immediate surrounding suburbs.; Homes with ≥Bachelor’s degree:; Richest zip codes: 28.0%; Medium zip codes: 27.1%; Poorest zip codes: 11.6% | Geographic location; - Richest zip codes (ref); - Medium zip codes; - Poorest zip codes | Branded foods | Inverse relationship (Richest vs. Poorest), Statistically significant; Relative price index, regression model (adjusted for store type, and distance to competitive environment), Adj R^2 = 0.78; Estimates (SE); Richest: Reference; Medium: 0.006 (0.008), p>0.1; Poorest: 0.019 (0.008), p<0.05
| | | Non-branded foods | No relationship, Statistically non-significant; Relative price index, regression model (adjusted for store type, and distance to competitive environment), Adj R^2 = 0.75; Estimates (SE); Richest: Reference; Medium: 0.006 (0.009), p>0.1; Poorest: 0.008 (0.014), p>0.1
Winkler, 2019 ^35^ | N=140; Analytic N = stores; Small and non-traditional food stores were randomly selected from lists of licensed grocery retailers in both cities. Of 157 eligible stores, 140 agreed to participate | SES proxy; - Lowest income; - Middle income; - Highest income | Apples | No relationship, Statistically non-significant; Price of Apples ($/item); Multivariate regression, adjusted for corporate status; Adjusted Mean (95% CI), N=56, p>0.05; POC dominant (Lowest income): $0.83 (0.67, 1.00); Racially mixed (Middle income): $0.84 (0.75, 0.93); White dominant (Highest income): $0.92 (0.83, 1.01)
| | | Bananas | No relationship, Statistically non-significant; Price of Bananas ($/item); Multivariate regression, adjusted for corporate status; Adjusted Mean (95% CI), N=64, p>0.05; POC dominant (Lowest income): $0.52 (0.44, 0.61); Racially mixed (Middle income): $0.45 (0.41, 0.49); White dominant (Highest income): $0.51 (0.46, 0.55)
| | | Lettuce | No relationship, Statistically non-significant; Price of Lettuce ($/item); Multivariate regression, adjusted for corporate status; Adjusted Mean (95% CI), N=15, p>0.05; POC dominant (Lowest income): $3.21 (1.47, 4.94); Racially mixed (Middle income): $3.37 (2.48, 4.27); White dominant (Highest income): $3.31 (2.71, 3.90)
| | | Onions | No relationship, Statistically non-significant; Price of Onions ($/item); Multivariate regression, adjusted for corporate status; Adjusted Mean (95% CI), N=25, p>0.05; POC dominant (Lowest income): $0.68 (0.13, 1.22); Racially mixed (Middle income): $0.70 (0.41, 0.99); White dominant (Highest income): $0.67 (0.38, 0.96)
| | | Oranges | No relationship, Statistically non-significant; Price of Oranges ($/item); Multivariate regression, adjusted for corporate status; Adjusted Mean (95% CI), N=47, p>0.05; POC dominant (Lowest income): $1.25 (1.00, 1.52); Racially mixed (Middle income): $0.84 (0.67, 1.01); White dominant (Highest income): $0.94 (0.76, 1.11)
| | | Tomatoes | No relationship, Statistically non-significant; Price of Tomatoes ($/item); Multivariate regression, adjusted for corporate status; Adjusted Mean (95% CI), N=18, p>0.05; POC dominant (Lowest income): $0.79 (0.00, 1.60); Racially mixed (Middle income): $1.30 (0.68, 1.93); White dominant (Highest income): $1.06 (0.52, 1.60)
Zenk, 2014 ^36^ | N=364; Analytic N = 364 WIC vendors in 7 seven northern Illinois counties (DeKalb, DuPage, Kane, Lee, Ogle, Winnebago, west suburban Cook [not including Chicago]).; Data were collected annually from each vendor. Analysis included all WIC vendors authorized in 20 | Income | Fruit | No relationship, Statistically non-significant; Fresh fruit; Multivariate regression, adjusted for vendor type, year of data collection, seasonality, population density, % other racial/ethnicity), Adj R^2 =0.25; Coefficient (SE); Neighborhood median HH income (1000s): <−0.01 (0.02), p=0.96; Canned fruit; Multivariate regression, adjusted for vendor type, year of data collection, seasonality, population density, % other racial/ethnicity), Adj R^2 =0.17; Coefficient (SE); Neighborhood median HH income (1000s): 0.01 (0.02), p=0.36; Frozen fruit; Multivariate regression, adjusted for vendor type, year of data collection, seasonality, population density, % other racial/ethnicity), Adj R^2 =0.29; Coefficient (SE); Neighborhood median HH income (1000s): 0.02 (0.02), p=0.17
| | | Vegetables | Direct relationship (canned), Statistically significant; No relationship (fresh and frozen), Statistically non-significant; Fresh vegetables; Multivariate regression, adjusted for vendor type, year of data collection, seasonality, population density, % other racial/ethnicity), Adj R^2 = 0.35; Coefficient (SE); Neighborhood median HH income (1000s): −0.02 (0.01), p=0.19; Canned vegetables; Multivariate regression, adjusted for vendor type, year of data collection, seasonality, population density, % other racial/ethnicity), Adj R^2 =0.61; Coefficient (SE); Neighborhood median HH income (1000s): 0.03 (0.01), p=0.002; Frozen vegetables; Multivariate regression, adjusted for vendor type, year of data collection, seasonality, population density, % other racial/ethnicity), Adj R^2 =0.26; Coefficient (SE); Neighborhood median HH income (1000s): 0.02 (0.01), p=0.14

a Abbreviations: ANOVA: Analysis of Variance; CSFII: USDA Continuing Survey of Food Intakes by Individuals; CX3: Communities of Excellence in Nutrition, Physical Activity and Obesity Prevention Project; DGA: Dietary Guidelines for Americans; F&V: Fruits and vegetables; FV-PI: Fruits and Vegetables Price Index; g: gram; gal: gallon; GEE: general estimation equation; HH: household; IQR: interquartile range; lb: pound; Ln: natural log; N: sample size; n/a: not applicable; NR: Not reported; NS: Statistically non-significant; ONQI: overall nutrition quality index; Oz: ounce; pc: piece; PIR: Poverty Income Ratio; POC: person of color; SD: standard deviation; SE: standard error; SEM: standard error of the mean; SES: Socioeconomic status; TFP: Thrifty Food Plan; USDA: United States Department of Agriculture; WIC: Special Supplemental Nutrition Program for Women, Infants, and Children; y: year

Table 1-c Risk of bias for observational studies examining income and food price^a^

Article | Confounding | Selection of participants | Classification of exposures | Deviations from intended exposures | Missing data | Outcome measurement | Selection of the reported result
Akbay, 2005^1^ | SERIOUS | NO INFORMATION | SERIOUS | LOW | NO INFORMATION | LOW | MODERATE
Andreyeva, 2008^2^ | SERIOUS | LOW | SERIOUS | MODERATE | LOW | LOW | MODERATE
Ard, 2010^3^ | MODERATE | LOW | SERIOUS | MODERATE | LOW | LOW | MODERATE
Beydoun, 2008^5^ | SERIOUS | MODERATE | LOW | LOW | LOW | MODERATE | SERIOUS
Beydoun, 2011^4^ | SERIOUS | MODERATE | LOW | LOW | LOW | MODERATE | SERIOUS
Block, 2006^6^ | SERIOUS | LOW | SERIOUS | LOW | MODERATE | LOW | MODERATE
Borja, 2019^7^ | SERIOUS | LOW | SERIOUS | MODERATE | LOW | LOW | MODERATE
Broda, 2009^8^ | MODERATE | LOW | LOW | LOW | NO INFORMATION | MODERATE | MODERATE
Cassady, 2007^9^ | SERIOUS | LOW | SERIOUS | LOW | LOW | LOW | SERIOUS
Chang, 2011^10^ | SERIOUS | LOW | SERIOUS | LOW | LOW | LOW | MODERATE
Chung, 1999^11^ | SERIOUS | LOW | SERIOUS | LOW | LOW | LOW | MODERATE
Colabianchi, 2021^37^ | MODERATE | LOW | SERIOUS | SERIOUS | LOW | LOW | MODERATE
Cole, 2010^12^ | SERIOUS | LOW | CRITICAL | LOW | SERIOUS | LOW | CRITICAL
Daepp, 2015^13^ | SERIOUS | NO INFORMATION | SERIOUS | LOW | SERIOUS | LOW | SERIOUS
Davis, 2005^14^ | SERIOUS | LOW | LOW | NO INFORMATION | NO INFORMATION | LOW | MODERATE
DeWeese, 2017^15^ | SERIOUS | LOW | SERIOUS | LOW | SERIOUS | LOW | MODERATE
Dunn, 2011^16^ | MODERATE | LOW | SERIOUS | LOW | MODERATE | LOW | MODERATE
French, 2010^17^ | SERIOUS | LOW | MODERATE | LOW | LOW | MODERATE | MODERATE
Gillespie, 2015^18^ | MODERATE | LOW | SERIOUS | LOW | LOW | LOW | SERIOUS
Gosliner, 2018^19^ | SERIOUS | SERIOUS | CRITICAL | LOW | MODERATE | MODERATE | MODERATE
Hardin-Fanning, 2015^20^ | SERIOUS | LOW | SERIOUS | LOW | LOW | LOW | SERIOUS
Hardin-Fanning, 2017^21^ | SERIOUS | LOW | CRITICAL | SERIOUS | LOW | LOW | MODERATE
Hatzenbuehler, 2012^22^ | MODERATE | LOW | SERIOUS | LOW | MODERATE | LOW | MODERATE
Hayes, 2000^23^ | SERIOUS | LOW | SERIOUS | LOW | MODERATE | LOW | MODERATE
Jetter, 2006^24^ | SERIOUS | LOW | SERIOUS | MODERATE | LOW | LOW | MODERATE
Jewell, 2019^25^ | MODERATE | LOW | SERIOUS | LOW | SERIOUS | LOW | SERIOUS
Kern, 2016^26^ | MODERATE | LOW | SERIOUS | LOW | LOW | LOW | SERIOUS
Kern, 2017^27^ | MODERATE | LOW | SERIOUS | LOW | LOW | LOW | SERIOUS
Leider, 2019^28^ | MODERATE | LOW | SERIOUS | LOW | MODERATE | LOW | SERIOUS
Leone, 2011^29^ | SERIOUS | LOW | SERIOUS | MODERATE | SERIOUS | LOW | MODERATE
Lopez-Class, 2010^30^ | SERIOUS | LOW | SERIOUS | LOW | SERIOUS | LOW | SERIOUS
Rimkus, 2015^31^ | SERIOUS | LOW | SERIOUS | LOW | MODERATE | LOW | SERIOUS
Smith, 2013^32^ | SERIOUS | LOW | CRITICAL | MODERATE | SERIOUS | LOW | MODERATE
Stewart, 2011^33^ | MODERATE | LOW | LOW | LOW | NO INFORMATION | MODERATE | MODERATE
Talukdar, 2008^34^ | SERIOUS | LOW | SERIOUS | MODERATE | LOW | LOW | MODERATE
Winkler, 2019^35^ | SERIOUS | LOW | SERIOUS | MODERATE | SERIOUS | LOW | SERIOUS
Zenk, 2014^36^ | MODERATE | MODERATE | SERIOUS | LOW | MODERATE | LOW | MODERATE

a Possible ratings of low, moderate, serious, critical, or no information determined using the “Risk of Bias for Nutrition Observational Studies” tool (RoB-NObs) ( Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC. )

## References of the articles included in the income and price of food rapid review

1 Akbay, C, Jones, E. Food consumption behavior of socioeconomic groups for private labels and national brands. Food Quality and Preference. 2005;16(7):621–631.doi. 10.1016/j.foodqual.2005.01.005.
2 Andreyeva, T, Blumenthal, . Availability and prices of foods across stores and neighborhoods: the case of New Haven, Connecticut. Health Aff (Millwood). 2008;27(5):1381–1388.doi: 10.1377/hlthaff.27.5.1381.18780928
3 Ard, J D, Perumean C, . Fruit and vegetable pricing by demographic factors in the Birmingham, Alabama, metropolitan area, 2004-2005. Prev Chronic Dis. 2010;7(4):A78.20550836
4 Beydoun, M A, Powell, . Food prices are associated with dietary quality, fast food consumption, and body mass index among U.S. children and adolescents. J Nutr. 2011;141(2):304–311.doi: 10.3945/jn.110.132613. Epub 2010 Dec 22.21178080
5 Beydoun, M A, Powell, L M, Wang, Y. The association of fast food, fruit and vegetable prices with dietary intakes among US adults: is there modification by family income? Soc Sci Med. 2008;66(11):2218–2229.doi: 10.1016/j.socscimed.2008.01.018. Epub 2008 Mar 3.18313824
6 Block, D, Kouba, J. A comparison of the availability and affordability of a market basket in two communities in the Chicago area. Public Health Nutr. 2006;9(7):837–845.doi: 10.1017/phn2005924.17010248
7 Borja, K, Dieringer, S. Availability of affordable healthy food in Hillsborough County, Florida. Journal of Public Affairs. 2019;19(3).doi. 10.1002/pa.1866.
8 Broda, C, Leibtag, E, Weinstein, D E. The role of prices in measuring the poor’s living standard. Journal of Economic Perspectives. 2009;23(2):77–97.20052301
9 Cassady, D, Jetter, K M, Culp, J. Is price a barrier to eating more fruits and vegetables for low-income families? J Am Diet Assoc. 2007;107(11):1909–1915.doi: 10.1016/j.jada.2007.08.015. Epub 2007 Oct 18.17964310
10 Chang, C H, Hooker, . Organic and Conventional Milk Purchase Behaviors in Central Ohio. Agribusiness. 2011;27(3):311–326.doi. 10.1002/agr.20269.
11 Chung, Chanjin, Myers, Jr Samuel L. Do the Poor Pay More for Food? An Analysis of Grocery Store Availability and Food Price Disparities. Journal of Consumer Affairs. 1999;33(2):276. http://ezproxyhhs.nihlibrary.nih.gov/login?url=http://search.ebscohost.com/login.aspx?direct=true&db=buh&AN=2440351&site=ehost-live&scope=site.
12 Cole, Shaun, Filomena, Susan, Morland, Kimberly. Analysis of Fruit and Vegetable Cost and Quality Among Racially Segregated Neighborhoods in Brooklyn, New York. Journal of Hunger & Environmental Nutrition. 2010;5(2):202–215.
13 Daepp, M. Prices and availability of healthy foods across St. Louis. American Economist. 2015;60(2):209–224.
14 Davis, David E, Leibtag, Ephraim S. INTERSTATE VARIATION IN WIC FOOD PACKAGE COSTS: THE ROLE OF FOOD PRICES, CASELOAD COMPOSITION, AND COST-CONTAINMENT PRACTICES. 2005:37.
15 DeWeese, R S, Ohri V, P. Cost of Children’s Healthy vs. Unhealthy Snacks Does Not Differ at Convenience Stores. J Nutr Educ Behav. 2017;49(3):241–243.e241.doi: 10.1016/j.jneb.2016.11.006. Epub 2017 Jan 7.28073622
16 Dunn, R A, Sharkey, . Socio-economic status, racial composition and the affordability of fresh fruits and vegetables in neighborhoods of a large rural region in Texas. Nutr J. 2011;10:6.doi: 10.1186/1475-2891-10-6.21244688
17 French, S A, Wall, M, Mitchell, N R. Household income differences in food sources and food items purchased. Int J Behav Nutr Phys Act. 2010;7:77.doi: 10.1186/1479-5868-7-77.20977738
18 Gillespie, Jeffrey, Hatzenbuehler, . The Impact of Neighborhood Income on the Cost of Energy-Dense and Nutrient-Dense Foods in Supermarkets. 2015;46(3):23.
19 Gosliner, W, Brown, . Availability, quality and price of produce in low-income neighbourhood food stores in California raise equity issues. Public Health Nutr. 2018;21(9):1639–1648.doi: 10.1017/S1368980018000058. Epub 2018 Mar 15.29540244
20 Hardin-Fanning, F, Rayens, M K. Food cost disparities in rural communities. Health Promot Pract. 2015;16(3):383–391.doi: 10.1177/1524839914554454. Epub 2014 Oct 10.25305093
21 Hardin-Fanning, F, Wiggins, A T. Food Costs Are Higher in Counties With Poor Health Rankings. J Cardiovasc Nurs. 2017;32(2):93–98.doi: 10.1097/JCN.0000000000000329.26977851
22 Hatzenbuehler, P, Gillespie, J, O’Neil, C. Does healthy food cost more in poor neighborhoods? An analysis of retail food cost and spatial competition. Agricultural and Resource Economics Review. 2012;41(1):43–56.
23 Hayes, Lashawn R. Are Prices Higher for the Poor in New York City? Journal of Consumer Policy. 2000;23(2):127–152. http://ezproxyhhs.nihlibrary.nih.gov/login?url=http://search.ebscohost.com/login.aspx?direct=true&db=buh&AN=3576727&site=ehost-live&scope=site.
24 Jetter, Karen M, Crespi, John M, Cassady, Diana. The Effects of the Spatial Distribution of Grocery Stores on Food Prices on Low Income Neighborhoods. 2006:18.
25 Jewell, M P, Lai, . Higher pricing of fresh produce is more likely in SNAP-Ed eligible neighborhoods when adjacent non-program eligible neighborhoods are mixed income. Prev Med Rep. 2019;14:100817.doi: 10.1016/j.pmedr.2019.01.021. eCollection 2019 Jun.30828538
26 Kern, D M, Auchincloss, . Neighbourhood variation in the price of soda relative to milk and its association with neighbourhood socio-economic status and race. Public Health Nutr. 2016;19(18):3386–3396.doi: 10.1017/S1368980016001579. Epub 2016 Jun 30.27357494
27 Kern, D M, Auchincloss, . Healthy and Unhealthy Food Prices across Neighborhoods and Their Association with Neighborhood Socioeconomic Status and Proportion Black/Hispanic. J Urban Health. 2017;94(4):494–505.doi: 10.1007/s11524-017-0168-8.28634777
28 Leider, J, Powell, L M. Sugar-sweetened beverage prices: Variations by beverage, food store, and neighborhood characteristics, 2017. Prev Med Rep. 2019;15:100883.doi: 10.1016/j.pmedr.2019.100883. eCollection 2019 Sep.31193242
29 Leone, A F, Rigby, . Leone . Store type and demographic influence on the availability and price of healthful foods, Leon County, Florida, 2008.. 8 (6), A140. Prev Chronic Dis. 2011;8(6):A140.22005633
30 Lopez-Class, M, Hosler, A S. Assessment of community food resources: A Latino neighborhood study in upstate New York. J Poverty. 2010;14(4):369–381.doi: 10.1080/10875549.2010.517070.22065468
31 Rimkus, L, Isgor, . Disparities in the Availability and Price of Low-Fat and Higher-Fat Milk in US Food Stores by Community Characteristics. J Acad Nutr Diet. 2015;115(12):1975–1985.doi: 10.1016/j.jand.2015.04.002. Epub 2015 Jun 2.26048532
32 Smith, M L, Sunil, . Disparities of food availability and affordability within convenience stores in Bexar County, Texas. J Environ Public Health. 2013;2013:782756.doi: 10.1155/2013/782756. Epub 2013 Jul 1.23935645
33 Stewart, H, Dong, D S. Variation in retail costs for fresh vegetables and salty snacks across communities in the United States. Food Policy. 2011;36(2):128–135.doi. 10.1016/j.foodpol.2010.10.002.
34 Talukdar, Debabrata. Cost of Being Poor: Retail Price and Consumer Price Search Differences across Inner-City and Suburban Neighborhoods. Journal of Consumer Research. 2008;35(3):457–471.
35 Winkler, M R, Lenk, . Variation in the food environment of small and non-traditional stores across racial segregation and corporate status. Public Health Nutr. 2019;22(9):1624–1634.doi: 10.1017/S1368980019000132. Epub 2019 Mar 8.30846012
36 Zenk, S N, Powell, . Impact of the revised Special Supplemental Nutrition Program for Women, Infants, and Children (WIC) food package policy on fruit and vegetable prices. J Acad Nutr Diet. 2014;114(2):288–296.doi: 10.1016/j.jand.2013.08.003. Epub 2013 Oct 30.24183996
37 Colabianchi, N, Antonakos, . The role of the built environment, food prices and neighborhood poverty in fruit and vegetable consumption: An instrumental variable analysis of the moving to opportunity experiment. Health Place. 2021;67:102491.doi: 10.1016/j.healthplace.2020.102491. Epub 2020 Dec 18.33348282