# Acknowledgments and funding

The NESR team members were involved in: establishing all aspects of the protocol, which presented the plan for examining the scientific evidence, including the inclusion and exclusion criteria; reviewing all studies that met the criteria they set; deliberating on the body of evidence for each question. The NESR team, with assistance from NEAT and Project Leadership, facilitated, executed, and documented the work necessary to ensure the reviews were completed in accordance with NESR methodology. NESR staff thanks NESR Lead Nutritionist Julie Obbaggy for her consultation and review of materials.

NESR staff thanks USDA’s NEAT, specifically TusaRebecca Pannucci, Clarissa (Claire) Brown, Hazel Hiza, Kristin Koegel, Kevin Kuczynski, Mark Lino, Emily Madan, Verena McClain, and Kevin Meyers Mathieu for their collaboration on all aspects of question protocols to ensure that the reviews completed as part of this project would be able to inform USDA’s Food Plans. NESR thanks them for their time and expertise.

NESR staff thanks USDA’s Director of NGAD Eve Stoody for her guidance, leadership, and support throughout this project.

NESR staff thank USDA’s Economic Research Service, specifically, Debbie Rubas, Andrea Carlson, Jordan Jones, Matthew MacLachlan, and Sabrina Young for their review of the literature search strategy for the rapid review on income and price of food, which subsequently informed the other evidence scans and rapid reviews. NESR thanks them for their time and expertise.

NESR staff thank Gisela Butera and Nancy Terry from National Institute of Health Library, Division of Library Services in the Office of Research Services for developing the initial literature search strategy for the rapid review on income and price of food. NESR thanks them for their time and expertise.