# Appendix 4-a Literature search strategy for the rapid review on income and time spent on food-at-home-related activities

Database: PubMed

Vendor: National Library of Medicine

Date of Search: 5/3/2021

Limits Used: Filters: Language English Publication Dates 2008 - 2021

Total = 2,401

Search # | Concept | Search String | N
#1 | Income | ( “Income”[Mesh] OR income*[tiab] OR “Socioeconomic Factors”[Mesh] OR socioeconomic*[tiab] OR socio-economic*[tiab] OR “social factor*”[tiab] OR “social condition*”[tiab] OR poverty[tiab] OR “Residence Characteristics”[Mesh] OR “Vulnerable Populations”[Mesh] OR “vulnerable population*”[tiab] OR “underserved population*”[tiab] OR “disadvantaged population*”[tiab] OR “Race Factors”[Mesh] OR “race factor*”[tiab] OR “Ethnic Groups”[Mesh] OR “ethnic group*”[tiab] OR “ethnic population*”[tiab] OR “Cross-Cultural Comparison”[Mesh] OR “cross-cultural”[tiab] OR transcultural[tiab] OR “Cultural Characteristics”[Mesh] OR “cultural characteristic*”[tiab] OR “Cultural Diversity”[Mesh] OR “culturally diverse”[tiab] OR “Food Supply”[Mesh] OR “food desert*”[tiab] OR “food insecurit*”[tiab] OR “food environment*”[tiab] OR “food access”[tiab] OR Urban[tiab] OR Rural[tiab] OR neighborhood[tiab] OR “Census tract”[tiab] OR “census block”[tiab] OR “food assistance”[MeSH Terms] OR “food assistance”[Tiab]) | 1,082,156
#2 | Time | (“Time Factors”[MeSH] OR “Time Management”[MeSH] OR Time[tiab]) | 4,181,306
#3 | Food Related Activities | (home*[tiab] OR domestic[tiab] OR family[tiab] OR families[tiab] OR house*[tiab]) AND (“Feeding Behavior”[Mesh] OR cooking[MeSH] OR Eating[MeSH] OR Food[MeSH] OR cook*[tiab] Or eat[tiab] OR eats[tiab] OR eating[tiab] OR eaten[tiab] OR Food[tiab] OR meal*[tiab] OR kitchen[tiab] OR clean*[tiab] OR dishwash*[tiab] OR (wash*[tiab] AND (dish[tiab] OR dishes[tiab]))) | 74,178
#4 | #1 AND #2 AND #3 | | 3,718
#5 | Publication, Geography, and species excludes | #1 AND #2 AND #3 NOT (; (letter[ptyp] OR editorial[ptyp] OR comment[ptyp] OR news[ptyp] OR “Congress”[Publication Type] OR “Consensus Development Conference”[Publication Type] OR editorial[tiab] OR commentary[tiab] OR “conference abstract*”[tiab] OR “systematic review*”[ti] OR “meta-analysis”[ptyp] OR “meta-analysis”[ti] OR “meta-analyses”[ti] OR “Review”[Publication Type] OR “Systematic Review”[Publication Type] OR “conference proceeding*”[tiab] OR “retracted publication”[ptyp] OR “retraction of publication”[ptyp] OR “retraction of publication”[tiab] OR “retraction notice”[ti] OR “retracted publication”[tiab] OR “Published Erratum”[Publication Type] OR corrigenda[tiab] OR corrigendum[tiab] OR errata[tiab] OR erratum[tiab] OR protocol[ti] OR protocols[ti] OR “case report”[ti] OR “case series”[ti] OR “Case Reports” [Publication Type]); NOT; (“Developing Countries”[Mesh] OR “developing countr*” OR “Under Developed Nation*” OR “low income countr*” OR “middle income countr*”OR “low-middle-income countr*” OR LMIC[tiab] OR “Europe”[Mesh] OR “Australia”[Mesh] OR “Asia”[Mesh] OR “Africa”[Mesh] OR “Mexico”[Mesh] OR “Islands”[Mesh] OR “Central America”[Mesh] OR “Latin America”[Mesh] OR “South America”[Mesh]); ); NOT; (“Animals”[Mesh] NOT; (“Animals”[Mesh] AND “Humans”[Mesh]); ) | 3,465
#6 | Filters | Filters: Language: English; Publication Dates: 2008-2021 | 2,401

Database: Business Source Premier

Vendor: EBSCO

Date of Search: 5/3/2021

Limits Used: Scholarly (Peer Reviewed) Journals; Published Date: 20080101-20211231; Document Type: Article; Language: English

Total = 950

Search # | Concept | Search String | N
#1 | Income | (DE “SOCIOECONOMIC factors”) OR socioeconomic* OR socio-economic* OR “social factor*” OR “social condition*” OR (DE “POVERTY”) OR poverty OR “vulnerable population*” OR “underserved population*” OR “disadvantaged population*” OR (DE “INCOME”) OR income* OR “race factor*” OR (DE “ECONOMIC conditions of ethnic groups”) OR “ethnic group*” OR “ethnic population*” OR “cross-cultural” OR transcultural OR “cultural characteristic*” OR “culturally diverse” OR (DE “FOOD supply”) OR “food desert*” OR “food insecurit*” OR “food environment*” OR “food access” OR (DE “METROPOLITAN areas”) OR Urban OR Rural OR neighborhood OR “Census tract” OR “census block” OR “food assistance” | 1,177,425
#2 | Time | (DE “TIME management” OR Time) | 1,359,692
#3 | Food Related Activities | ((home* OR domestic OR family OR families OR house*) AND (DE “FOOD safety” OR cook* OR eat* OR Food OR meal* OR kitchen OR clean* OR dishwash* OR (wash* AND (dish OR dishes))) | 127,582
#4 | #1 AND #2 AND #3 | | 1,856
#5 | Filters | Limiters - Scholarly (Peer Reviewed) Journals; Published Date: 20080101-20211231; Document Type: Article; Language: English | 950

Database: Web of Science: Core Collection

Vendor: Clarivate Analytics

Date of Search: 5/3/2021

Limits Used:

Total = 3,545

Search # | Concept | Search String | N
#1 | Income | TS=(socioeconomic* OR socio-economic* OR “social factor*” OR “social condition*” OR poverty OR “residence characteristics” OR “vulnerable population*” OR “underserved population*” OR “disadvantaged population*” OR income* OR “race factor*” OR “ethnic group*” OR “ethnic population*” OR “cross-cultural” OR transcultural OR “cultural characteristic*” OR “culturally diverse” OR “food desert*” OR “food insecurit*” OR Urban OR Rural OR neighborhood OR “Census tract” OR “census block” OR “food assistance”) | 1,019,047
#2 | Time | TS=time | 6,476,056
#3 | Food Related Activities | TS=((home* OR domestic OR family OR families OR house*) AND (“FOOD safety” OR cook* OR eat* OR Food OR meal* OR kitchen OR clean* OR dishwash* OR (wash* AND (dish OR dishes)))) | 119,957
#4 | #1 AND #2 AND #3 | | 5,569
#5 | Non-United States | CU=(“developing countr*” OR “under developed nation*” OR “low income countr*” OR “middle income; countr*” OR “low-middle income countr*” OR LMIC; OR Europe OR Australia OR Asia OR Africa OR Mexico OR Islands OR “Central America” OR “Latin America” OR “South America”) | 2,037,499
#6 | #4 NOT #5 | | 4,920
#7 | Publication Excludes | TS=(editorial OR commentary OR “conference abstract*” OR “conference proceeding*”[tiab] OR “retraction of publication” OR “retracted publication” OR corrigenda[tiab] OR corrigendum[tiab] OR errat a OR erratum OR “case reports” ) OR TI=(“systematic review*” OR “meta-analysis”; OR “meta analyses” OR protocol OR protocols; OR “retraction notice” OR “case report” OR; “case series”) | 708,261
#8 | #6 NOT #5 | | 4,920
#9 | | Years: 2008-2021; Publication Types: Articles, Early Access | 3,545

## Grey Literature Search

### Google Scholar

(Income OR resources OR poverty OR socioeconomic) AND time AND ((home OR domestic OR family OR house) AND (eating OR meals OR cooking OR cleaning OR washing dishes))

Limits: Date published: 2008-2021;

Date Searched: 5/14/2021

Results: 40, limited to 4 pages

### Google

site:.gov AND (Income OR resources OR poverty OR socioeconomic) AND (time OR time spent) AND ((home OR domestic OR family) AND (meal preparation OR meals OR cooking OR cleaning))

Limits: Include Omitted results

Date Searched: 5/14/2021

Results: 10, limited to 1 page

### Ag Econ

Any of the words: Income resources poverty socioeconomic

AND

Any of the words: Time

AND

Any of the words: “Food at home” “at home meals” “meals at home” “cooking at home” “family cooking” “family meals” “meal preparation” “food preparation”

Limits: added since 2008

Date Searched: 5/14/2021

Results: 60, limited to 6 pages