# Appendix 3-b Excluded articles for the rapid review on diet cost and HEI

The following table lists the articles excluded after full-text screening for this rapid review question. At least 1 reason for exclusion is provided for each article, though this may not reflect all possible reasons. Information about articles excluded after title and abstract screening is available upon request.

# | Bibliography | Exclusion rationale
1 | affordable healthy food: Topics by Science.gov, 2021 | Publication status
2 | Federal Register, Volume 85 Issue 228 (Wednesday, November 25, 2020). 2020 | Publication status
3 | Healthy Eating Index (HEI) \| USDA-FNS. 2021 | Publication status
4 | Research Rundown: USDA School Nutrition and Meal Cost Study. 2019; | Pubilcation status
5 | TFCO Access to Healthy Affordable Food | Outcome, Study design
6 | Acheampong, I.,Haldeman, L. Are nutrition knowledge, attitudes, and beliefs associated with obesity among low-income Hispanic and African American women caretakers?. J Obes. 2013; 2013 :123901. doi: 10.1155/2013/123901. | Intervention/Exposure, Outcome
7 | Aggarwal, A.,Drewnowski, A. Plant- and animal-protein diets in relation to sociodemographic drivers, quality, and cost: findings from the Seattle Obesity Study. Am J Clin Nutr. 2019; 110 (2):451-460. doi: 10.1093/ajcn/nqz064. | Outcome
8 | Aggarwal, A.,Monsivais, P.,Cook, A. J.,Drewnowski, A. Does diet cost mediate the relation between socioeconomic position and diet quality?. Eur J Clin Nutr. 2011; 65 (9):1059-66. doi: 10.1038/ejcn.2011.72. | Outcome
9 | Aggarwal, A.,Monsivais, P.,Cook, A. J.,Drewnowski, A. Positive attitude toward healthy eating predicts higher diet quality at all cost levels of supermarkets. J Acad Nutr Diet. 2014; 114 (2):266-72. doi: 10.1016/j.jand.2013.06.006. | Outcome
10 | Aggarwal, A.,Monsivais, P.,Drewnowski, A. Nutrient intakes linked to better health outcomes are associated with higher diet costs in the US. PLoS One. 2012; 7 (5):e37533. doi: 10.1371/journal.pone.0037533. | Outcome
11 | Aggarwal, A.,Rehm, C. D.,Monsivais, P.,Drewnowski, A. Importance of taste, nutrition, cost and convenience in relation to diet quality: Evidence of nutrition resilience among US adults using National Health and Nutrition Examination Survey (NHANES) 2007-2010. Prev Med. 2016; 90 :184-92. doi: 10.1016/j.ypmed.2016.06.030. | Intervention/Exposure
12 | Amenyenu, Anonya,Tegegne, Fisseha,Singh, Surendra P.,Ekanem, Enefiok. Knowledge of 2005 Dietary Guidelines and Food Consumption Habits of African-Americans in Tennessee. Journal of Food Distribution Research. 2010; 41 (1):1-4. | Intervention/Exposure, Data date range
13 | Appelhans, B. M.,French, S. A.,Tangney, C. C.,Powell, L. M.,Wang, Y. To what extent do food purchases reflect shoppers’ diet quality and nutrient intake?. Int J Behav Nutr Phys Act. 2017; 14 (1):46. doi: 10.1186/s12966-017-0502-2. | Intervention/Exposure
14 | Appelhans, B. M.,Milliron, B. J.,Woolf, K.,Johnson, T. J.,Pagoto, S. L.,Schneider, K. L.,Whited, M. C.,Ventrelle, J. C. Socioeconomic status, energy cost, and nutrient content of supermarket food purchases. Am J Prev Med. 2012; 42 (4):398-402. doi: 10.1016/j.amepre.2011.12.007. | Outcome
15 | Appelhans, B. M.,Tangney, C. C.,French, S. A.,Crane, M. M.,Wang, Y. Delay discounting and household food purchasing decisions: The SHoPPER study. Health Psychol. 2019; 38 (4):334-342. doi: 10.1037/hea0000727. | Intervention/Exposure
16 | Basu, S.,Gardner, C. D.,White, J. S.,Rigdon, J.,Carroll, M. M.,Akers, M.,Seligman, H. K. Effects Of Alternative Food Voucher Delivery Strategies On Nutrition Among Low-Income Adults. Health Aff (Millwood). 2019; 38 (4):577-584. doi: 10.1377/hlthaff.2018.05405. | Intervention/Exposure
17 | Basu, S.,Seligman, H.,Bhattacharya, J. Nutritional policy changes in the supplemental nutrition assistance program: a microsimulation and cost-effectiveness analysis. Med Decis Making. 2013; 33 (7):937-48. doi: 10.1177/0272989X13493971. | Intervention/Exposure
18 | Baudry, J.,Pointereau, P.,Seconda, L.,Vidal, R.,Taupier-Letage, B.,Langevin, B.,Alles, B.,Galan, P.,Hercberg, S.,Amiot, M. J.,Boizot-Szantai, C.,Hamza, O.,Cravedi, J. P.,Debrauwer, L.,Soler, L. G.,Lairon, D.,Kesse-Guyot, E. Improvement of diet sustainability with increased level of organic food in the diet: findings from the BioNutriNet cohort. American Journal of Clinical Nutrition. 2019; 109 (4):1173-1188. doi: 10.1093/ajcn/nqy361. | Country
19 | Beheshti, R.,Jones-Smith, J. C.,Igusa, T. Taking dietary habits into account: A computational method for modeling food choices that goes beyond price. PLoS One. 2017; 12 (5):e0178348. doi: 10.1371/journal.pone.0178348. | Outcome, Data date range
20 | Bernstein, A. M.,Bloom, D. E.,Rosner, B. A.,Franz, M.,Willett, W. C. Relation of food cost to healthfulness of diet among US women. Am J Clin Nutr. 2010; 92 (5):1197-203. doi: 10.3945/ajcn.2010.29854. | Data date range
21 | Bessems, Kmhh,Linssen, E.,Lomme, M.,Van Assema, P. The Effectiveness of the Good Affordable Food Intervention for Adults with Low Socioeconomic Status and Small Incomes. International Journal of Environmental Research and Public Health. 2020; 17 (7) doi: 10.3390/ijerph17072535. | Outcome
22 | Beydoun, M. A.,Nkodo, A.,Fanelli-Kuczmarski, M. T.,Maldonado, A. I.,Beydoun, H. A.,Popkin, B. M.,Evans, M. K.,Zonderman, A. B. Longitudinal Associations between Monetary Value of the Diet, DASH Diet Score and the Allostatic Load among Middle-Aged Urban Adults. Nutrients. 2019; 11 (10) doi: 10.3390/nu11102360. | Outcome
23 | Beydoun, M. A.,Powell, L. M.,Chen, X.,Wang, Y. Food prices are associated with dietary quality, fast food consumption, and body mass index among U.S. children and adolescents. J Nutr. 2011; 141 (2):304-11. doi: 10.3945/jn.110.132613. | Intervention/Exposure, Data date range
24 | Beydoun, M. A.,Powell, L. M.,Wang, Y. Reduced away-from-home food expenditure and better nutrition knowledge and belief can improve quality of dietary intake among US adults. Public Health Nutr. 2009; 12 (3):369-81. doi: 10.1017/S1368980008002140. | Intervention/Exposure, Data date range
25 | Beydoun, M. A.,Powell, L. M.,Wang, Y. The association of fast food, fruit and vegetable prices with dietary intakes among US adults: is there modification by family income?. Soc Sci Med. 2008; 66 (11):2218-29. doi: 10.1016/j.socscimed.2008.01.018. | Intervention/Exposure, Data date range
26 | Beydoun, M. A.,Wang, Y. How do socio-economic status, perceived economic barriers and nutritional benefits affect quality of dietary intake among US adults?. Eur J Clin Nutr. 2008; 62 (3):303-13. doi: 10.1038/sj.ejcn.1602700. | Data date range
27 | Bouis, H. E.,Eozenou, P.,Rahman, A. Food prices, household income, and resource allocation: Socioeconomic perspectives on their effects on dietary quality and nutritional status. Food and Nutrition Bulletin. 2011; 32 (1):S14-S23. doi: 10.1177/15648265110321S103. | Country
28 | Brewster, P. J.,Durward, C. M.,Hurdle, J. F.,Stoddard, G. J.,Guenther, P. M. The Grocery Purchase Quality Index-2016 Performs Similarly to the Healthy Eating Index-2015 in a National Survey of Household Food Purchases. J Acad Nutr Diet. 2019; 119 (1):45-56. doi: 10.1016/j.jand.2018.08.165. | Intervention/Exposure
29 | Brewster, P. J.,Guenther, P. M.,Jordan, K. C.,Hurdle, J. F. The Grocery Purchase Quality Index-2016: An innovative approach to assessing grocery food purchases. Journal of Food Composition and Analysis. 2017; 64 :119-126. doi: 10.1016/j.jfca.2017.07.012. | Intervention/Exposure
30 | Carlson, A.,Dong, D. S.,Lino, M. Association between Total Diet Cost and Diet Quality Is Limited. Journal of Agricultural and Resource Economics. 2014; 39 (1):47-68. | Data date range
31 | Carlson, A.,Frazao, E. Food costs, diet quality and energy balance in the United States. Physiology & Behavior. 2014; 134 :20-31. doi: 10.1016/j.physbeh.2014.03.001. | Data date range
32 | Carlson, Andrea,Dong, Diansheng,Lino, Mark. ARE THE TOTAL DAILY COST OF FOOD AND DIET QUALITY RELATED: A RANDOM EFFECTS PANEL DATA ANALYSIS. . 2010; :25. doi: 10.22004/ag.econ.116395. | Data date range
33 | Carlson, Andrea,Lino, Mark,Fungwe, Thomas V.,Guenther, Patricia M. Eating a Healthy Diet: Is Cost a Major Factor?. . 2009; doi: 10.22004/ag.econ.49259. | Data date range
34 | Caspi, C. E.,Lenk, K.,Pelletier, J. E.,Barnes, T. L.,Harnack, L.,Erickson, D. J.,Laska, M. N. Association between store food environment and customer purchases in small grocery stores, gas-marts, pharmacies and dollar stores. Int J Behav Nutr Phys Act. 2017; 14 (1):76. doi: 10.1186/s12966-017-0531-x. | Intervention/Exposure
35 | Chen, Xiu,Kaiser, Harry M.,Rickard, Bradley J. The Salience of Excise vs.. Sales Taxes on Healthy Eating: An Experimental Study. . 2014; :39. doi: 10.22004/ag.econ.180111. | Outcome
36 | Chrisinger, B. W.,Kallan, M. J.,Whiteman, E. D.,Hillier, A. Where do U.S. households purchase healthy foods? An analysis of food-at-home purchases across different types of retailers in a nationally representative dataset. Prev Med. 2018; 112 :15-22. doi: 10.1016/j.ypmed.2018.03.015. | Intervention/Exposure
37 | Clark, R. L.,Famodu, O. A.,Barr, M. L.,Hagedorn, R. L.,Ruseski, J.,White, J. A.,Warner, C. M.,Morrell, A. M.,Murray, P. J.,Olfert, I. M.,McFadden, J. W.,Downes, M. T.,Colby, S. E.,Olfert, M. D. Monetary Cost of the MyPlate Diet in Young Adults: Higher Expenses Associated with Increased Fruit and Vegetable Consumption. J Nutr Metab. 2019; 2019 :2790963. doi: 10.1155/2019/2790963. | Outcome
38 | Collins, A. M.,Klerman, J. A. Improving Nutrition by Increasing Supplemental Nutrition Assistance Program Benefits. Am J Prev Med. 2017; 52 (2S2):S179-S185. doi: 10.1016/j.amepre.2016.08.032. | Outcome
39 | Courtemanche, Charles,Denteh, Augustine,Tchernis, Rusty. Estimating the Associations between SNAP and Food Insecurity, Obesity, and Food Purchases with Imperfect Administrative Measures of Participation. Southern Economic Journal. 2019; 86 (1):202-228. doi: 10.1002/soej.12364. | Intervention/Exposure
40 | Crane, M. M.,Tangney, C. C.,French, S. A.,Wang, Y.,Appelhans, B. M. Gender Comparison of the Diet Quality and Sources of Food Purchases Made by Urban Primary Household Food Purchasers. J Nutr Educ Behav. 2019; 51 (2):199-204. doi: 10.1016/j.jneb.2018.07.016. | Intervention/Exposure
41 | D’Angelo, H.,Suratkar, S.,Song, H. J.,Stauffer, E.,Gittelsohn, J. Access to food source and food source use are associated with healthy and unhealthy food-purchasing behaviours among low-income African-American adults in Baltimore City. Public Health Nutrition. 2011; 14 (9):1632-1639. doi: 10.1017/S1368980011000498. | Outcome
42 | Darmon, N.,Lacroix, A.,Muller, L.,Ruffieux, B. Food price policies improve diet quality while increasing socioeconomic inequalities in nutrition. Int J Behav Nutr Phys Act. 2014; 11 :66. doi: 10.1186/1479-5868-11-66. | Outcome
43 | Davis, G. C.,Carlson, A. The inverse relationship between food price and energy density: is it spurious?. Public Health Nutr. 2015; 18 (6):1091-7. doi: 10.1017/S1368980014001098. | Outcome
44 | Deierlein, A. L.,Morland, K. B.,Scanlin, K.,Wong, S.,Spark, A. Diet quality of urban older adults age 60 to 99 years: the Cardiovascular Health of Seniors and Built Environment Study. J Acad Nutr Diet. 2014; 114 (2):279-87. doi: 10.1016/j.jand.2013.09.002. | Intervention/Exposure
45 | Dellava, Jocilyn E,Bulik, Cynthia M,Popkin, Barry M. Price changes alone are not adequate to produce long-term dietary change. The Journal of nutrition. 2010; 140 (10):1887-1891. | Country
46 | Dhakal, C. K.,Khadka, S. Heterogeneities in Consumer Diet Quality and Health Outcomes of Consumers by Store Choice and Income. Nutrients. 2021; 13 (4) doi: 10.3390/nu13041046. | Intervention/Exposure
47 | Drewnowski, A. Nutrient density: addressing the challenge of obesity. Br J Nutr. 2018; 120 (s1):S8-S14. doi: 10.1017/S0007114517002240. | Study design
48 | Drewnowski, A. Nutrition Economics: How to Eat Better for Less. J Nutr Sci Vitaminol (Tokyo). 2015; 61 Suppl :S69-71. doi: 10.3177/jnsv.61.S69. | Study design
49 | Drewnowski, A. The economics of food choice behavior: why poverty and obesity are linked. Nestle Nutr Inst Workshop Ser. 2012; 73 :95-112. doi: 10.1159/000341303. | Outcome, Study design
50 | Drewnowski, A.,Kawachi, I. Diets and Health: How Food Decisions Are Shaped by Biology, Economics, Geography, and Social Interactions. Big Data. 2015; 3 (3):193-197. doi: 10.1089/big.2015.0014. | Study design
51 | D’Souza, Anna,Jolliffe, Dean. Food Insecurity in Vulnerable Populations: Coping with Food Price Shocks in Afghanistan. American Journal of Agricultural Economics. 2014; 96 (3):790-812. doi: 10.1093/ajae/aat089. | Country
52 | Duffey, K. J.,Gordon-Larsen, P.,Shikany, J. M.,Guilkey, D.,Jacobs, D. R., Jr.,Popkin, B. M. Food price and diet and health outcomes: 20 years of the CARDIA Study. Arch Intern Med. 2010; 170 (5):420-6. doi: 10.1001/archinternmed.2009.545. | Data date range
53 | Egeland, G. M.,Williamson-Bathory, L.,Johnson-Down, L.,Sobol, I. Traditional food and monetary access to market-food: correlates of food insecurity among Inuit preschoolers. Int J Circumpolar Health. 2011; 70 (4):373-83. doi: 10.3402/ijch.v70i4.17836. | Country
54 | Emond, J. A.,Madanat, H. N.,Ayala, G. X. Do Latino and non-Latino grocery stores differ in the availability and affordability of healthy food items in a low-income, metropolitan region?. Public Health Nutrition. 2012; 15 (2):360-369. doi: 10.1017/S1368980011001169. | Intervention/Exposure, Outcome
55 | Epstein, L. H.,Finkelstein, E. A.,Katz, D. L.,Jankowiak, N.,Pudlewski, C.,Paluch, R. A. Effects of nutrient profiling and price changes based on NuVal(R) scores on food purchasing in an online experimental supermarket. Public Health Nutr. 2016; 19 (12):2157-64. doi: 10.1017/S1368980015002931. | Outcome
56 | Ford, C. N.,Poti, J. M.,Ng, S. W.,Popkin, B. M. SSB taxes and diet quality in US preschoolers: estimated changes in the 2010 Healthy Eating Index. Pediatr Obes. 2017; 12 (2):146-154. doi: 10.1111/ijpo.12121. | Intervention/Exposure
57 | Forrestal, S.,Potamites, E.,Guthrie, J.,Paxton, N. Associations among Food Security, School Meal Participation, and Students’ Diet Quality in the First School Nutrition and Meal Cost Study. Nutrients. 2021; 13 (2) doi: 10.3390/nu13020307. | Intervention/Exposure
58 | Franckle, R. L.,Thorndike, A. N.,Moran, A. J.,Hou, T.,Blue, D.,Greene, J. C.,Bleich, S. N.,Block, J. P.,Polacsek, M.,Rimm, E. B. Supermarket Purchases Over the Supplemental Nutrition Assistance Program Benefit Month: A Comparison Between Participants and Nonparticipants. Am J Prev Med. 2019; 57 (6):800-807. doi: 10.1016/j.amepre.2019.07.025. | Outcome
59 | Freedman, D. A.,Bell, B. A.,Clark, J.,Ngendahimana, D.,Borawski, E.,Trapl, E.,Pike, S.,Sehgal, A. R. Small Improvements in an Urban Food Environment Resulted in No Changes in Diet Among Residents. J Community Health. 2021; 46 (1):1-12. doi: 10.1007/s10900-020-00805-z. | Intervention/Exposure
60 | French, S. A.,Tangney, C. C.,Crane, M. M.,Wang, Y.,Appelhans, B. M. Nutrition quality of food purchases varies by household income: the SHoPPER study. BMC Public Health. 2019; 19 (1):231. doi: 10.1186/s12889-019-6546-2. | Outcome
61 | French, S. A.,Wall, M.,Mitchell, N. R.,Shimotsu, S. T.,Welsh, E. Annotated receipts capture household food purchases from a broad range of sources. Int J Behav Nutr Phys Act. 2009; 6 :37. doi: 10.1186/1479-5868-6-37. | Outcome
62 | Fulgoni, V., 3rd,Drewnowski, A. An Economic Gap Between the Recommended Healthy Food Patterns and Existing Diets of Minority Groups in the US National Health and Nutrition Examination Survey 2013-14. Front Nutr. 2019; 6 :37. doi: 10.3389/fnut.2019.00037. | Outcome
63 | Gao, Zhifeng,Yu, Xiaohua,Lee, Jonq-Ying. Consumer demand for diet quality: evidence from the healthy eating index Consumer demand for diet quality: evidence from the healthy eating index. Australian Journal of Agricultural & Resource Economics. 2013; 57 (3):301-319. doi: 10.1111/j.1467-8489.2012.00619.x. | Intervention/Exposure
64 | Glickman, A. R.,Clark, J. K.,Freedman, D. A. A relational approach to evaluate food environments finds that the proximate food environment matters for those who use it. Health Place. 2021; 69 :102564. doi: 10.1016/j.healthplace.2021.102564. | Intervention/Exposure
65 | Gregory, Christian ,Ver Ploeg, Michele ,Andrews, Margaret ,Coleman-Jensen, Alisha . Supplemental Nutrition Assistance Program (SNAP) Participation Leads to Modest Changes in Diet Quality. . 2013; :36. doi: 10.22004/ag.econ.262225. | Intervention/Exposure
66 | Guenther, P. M.,Luick, B. R. Improved Overall Quality of Diets Reported by Expanded Food and Nutrition Education Program Participants in the Mountain Region. J Nutr Educ Behav. 2015; 47 (5):421-6 e1. doi: 10.1016/j.jneb.2015.05.001. | Comparator
67 | Gustafson, A.,Jilcott Pitts, S.,McDonald, J.,Ford, H.,Connelly, P.,Gillespie, R.,Liu, E.,Bush, H.,Brancato, C.,Babatande, T.,Mullins, J. Direct Effects of the Home, School, and Consumer Food Environments on the Association between Food Purchasing Patterns and Dietary Intake among Rural Adolescents in Kentucky and North Carolina, 2017. Int J Environ Res Public Health. 2017; 14 (10) doi: 10.3390/ijerph14101255. | Outcome
68 | Hakansson, A.,Andersson, H. S.,Granfeldt, Y. Diet inequality prevails among consumers interested and knowledgeable in nutrition. Food Nutr Res. 2015; 59 :27601. doi: 10.3402/fnr.v59.27601. | Outcome
69 | Hamad, R.,Templeton, Z. S.,Schoemaker, L.,Zhao, M.,Bhattacharya, J. Comparing demographic and health characteristics of new and existing SNAP recipients: application of a machine learning algorithm. Am J Clin Nutr. 2019; 109 (4):1164-1172. doi: 10.1093/ajcn/nqy355. | Intervention/Exposure
70 | Han, H. Y.,Paquet, C.,Dube, L.,Nielsen, D. E. Diet Quality and Food Prices Modify Associations between Genetic Susceptibility to Obesity and Adiposity Outcomes. Nutrients. 2020; 12 (11) doi: 10.3390/nu12113349. | Country
71 | Harnack, L.,Oakes, J. M.,Elbel, B.,Beatty, T.,Rydell, S.,French, S. Effects of Subsidies and Prohibitions on Nutrition in a Food Benefit Program: A Randomized Clinical Trial. JAMA Intern Med. 2016; 176 (11):1610-1618. doi: 10.1001/jamainternmed.2016.5633. | Intervention/Exposure, Outcome
72 | Hatzenbuehler, Patrick L.,Gillespie, Jeffrey M.,O’Neil, Carol E. The Cost of Dietary Variety: A Case of Fruit and Vegetables. Journal of Food Distribution Research. 2011; 42 (3):1-13. | Outcome
73 | Hilmers, A.,Chen, T. A.,Dave, J. M.,Thompson, D.,Cullen, K. W. Supplemental Nutrition Assistance Program participation did not help low income Hispanic women in Texas meet the dietary guidelines. Prev Med. 2014; 62 :44-8. doi: 10.1016/j.ypmed.2014.01.016. | Intervention/Exposure, Outcome
74 | Huffman, F. G.,Vaccaro, J. A.,Zarini, G. G.,Dixon, Z. Comparison of Two Indices of Diet Quality with Acculturation Factors and Demographics in Haitian Americans. Ecology of Food and Nutrition. 2014; 53 (1):42-57. doi: 10.1080/03670244.2013.774674. | Intervention/Exposure
75 | Hyder, J. A.,Thomson, C. A.,Natarajan, L.,Madlensky, L.,Pu, M.,Emond, J.,Kealey, S.,Rock, C. L.,Flatt, S. W.,Pierce, J. P.,Whel Study Group. Adopting a plant-based diet minimally increased food costs in WHEL Study. Am J Health Behav. 2009; 33 (5):530-9. doi: 10.5993/ajhb.33.5.6. | Outcome, Data date range
76 | Jahns, L.,McDonald, L.,Wadsworth, A.,Morin, C.,Liu, Y.,Nicklas, T. Barriers and facilitators to following the Dietary Guidelines for Americans reported by rural, Northern Plains American-Indian children. Public Health Nutr. 2015; 18 (3):482-9. doi: 10.1017/S136898001400041X. | Intervention/Exposure, Outcome
77 | Jetter, K. M.,Adkins, J.,Cortez, S.,Hopper, G. K., Jr.,Shively, V.,Styne, D. M. Yes We Can: Eating Healthy on a Limited Budget. J Nutr Educ Behav. 2019; 51 (3):268-276. doi: 10.1016/j.jneb.2018.12.002. | Intervention/Exposure, Outcome
78 | Jilcott Pitts, S. B.,Wu, Q.,Truesdale, K. P.,Rafferty, A. P.,Haynes-Maslow, L.,Boys, K. A.,McGuirt, J. T.,Fleischhacker, S.,Johnson, N.,Kaur, A. P.,Bell, R. A.,Ammerman, A. S.,Laska, M. N. A four-year observational study to examine the dietary impact of the North Carolina Healthy Food Small Retailer Program, 2017-2020. Int J Behav Nutr Phys Act. 2021; 18 (1):44. doi: 10.1186/s12966-021-01109-8. | Intervention/Exposure
79 | Keim, N. L.,Forester, S. M.,Lyly, M.,Aaron, G. J.,Townsend, M. S. Vegetable variety is a key to improved diet quality in low-income women in California. J Acad Nutr Diet. 2014; 114 (3):430-5. doi: 10.1016/j.jand.2013.07.026. | Intervention/Exposure, Outcome
80 | Kell, K. P.,Judd, S. E.,Pearson, K. E.,Shikany, J. M.,Fernandez, J. R. Associations between socio-economic status and dietary patterns in US black and white adults. British Journal of Nutrition. 2015; 113 (11):1792-1799. doi: 10.1017/S0007114515000938. | Intervention/Exposure, Outcome
81 | Kern, D. M.,Auchincloss, A. H.,Robinson, L. F.,Stehr, M. F.,Pham-Kanter, G. Healthy and Unhealthy Food Prices across Neighborhoods and Their Association with Neighborhood Socioeconomic Status and Proportion Black/Hispanic. Journal of Urban Health-Bulletin of the New York Academy of Medicine. 2017; 94 (4):494-505. doi: 10.1007/s11524-017-0168-8. | Outcome
82 | Kern, D. M.,Auchincloss, A. H.,Stehr, M. F.,Roux, A. V. D.,Moore, L. V.,Kanter, G. P.,Robinson, L. F. Neighborhood Prices of Healthier and Unhealthier Foods and Associations with Diet Quality: Evidence from the Multi-Ethnic Study of Atherosclerosis. Int J Environ Res Public Health. 2017; 14 (11) doi: 10.3390/ijerph14111394. | Intervention/Exposure, Comparator
83 | Klassen, A. C.,Smith, K. C.,Black, M. M.,Caulfield, L. E. Mixed method approaches to understanding cancer-related dietary risk reduction among public housing residents. J Urban Health. 2009; 86 (4):624-40. doi: 10.1007/s11524-009-9352-9. | Intervention/Exposure, Data date range
84 | Kroshus, E. Gender, marital status, and commercially prepared food expenditure. J Nutr Educ Behav. 2008; 40 (6):355-60. doi: 10.1016/j.jneb.2008.05.012. | Outcome
85 | Leone, A. F.,Rigby, S.,Betterley, C.,Park, S.,Kurtz, H.,Johnson, M. A.,Lee, J. S. Store type and demographic influence on the availability and price of healthful foods, Leon County, Florida, 2008. Prev Chronic Dis. 2011; 8 (6):A140. | Outcome
86 | Liese, A. D.,Ma, X.,Hutto, B.,Sharpe, P. A.,Bell, B. A.,Wilcox, S. Food Shopping and Acquisition Behaviors in Relation to BMI among Residents of Low-Income Communities in South Carolina. Int J Environ Res Public Health. 2017; 14 (9) doi: 10.3390/ijerph14091075. | Outcome
87 | Lin, Biing-Hwan. Nutrition and Health Characteristics of Low-Income Populations: Healthy Eating Index. . 2005; :4. doi: 10.22004/ag.econ.33617. | Data date range
88 | Litvak, J.,Parekh, N.,Juul, F.,Deierlein, A. Food assistance programs and income are associated with the diet quality of grocery purchases for households consisting of women of reproductive age or young children. Prev Med. 2020; 138 :106149. doi: 10.1016/j.ypmed.2020.106149. | Intervention/Exposure
89 | Mabli J, Castner L, Ohls J, Fox MK, Crepinsek MK, Condon E. Food Expenditures and Diet Quality Among Low-Income Households and Individuals. . 2010; | Data date range
90 | Maillot, M.,Drewnowski, A. Energy allowances for solid fats and added sugars in nutritionally adequate U.S. diets estimated at 17-33% by a linear programming model. J Nutr. 2011; 141 (2):333-40. doi: 10.3945/jn.110.131920. | Outcome
91 | Mancino, Lisa,Todd, Jessica E.,Scharadin, Benjamin. USDA’s National Household Food Acquisition and Purchase Survey: Methodology for Imputing Missing Quantities To Calculate Healthy Eating Index-2010 Scores and Sort Foods Into ERS Food Groups. . 2018; doi: 10.22004/ag.econ.276252. | Intervention/Exposure, Comparator
92 | Masset, G.,Monsivais, P.,Maillot, M.,Darmon, N.,Drewnowski, A. Diet optimization methods can help translate dietary guidelines into a cancer prevention food plan. J Nutr. 2009; 139 (8):1541-8. doi: 10.3945/jn.109.104398. | Outcome
93 | McClain, A. C.,Tucker, K. L.,Falcon, L. M.,Mattei, J. Food insecurity and dietary intake by Supplemental Nutrition Assistance Program participation status among mainland US Puerto Rican adults after the 2009 American Recovery and Reinvestment Act. Public Health Nutrition. 2019; 22 (16):2989-2998. doi: 10.1017/S1368980019002209. | Intervention/Exposure
94 | McCurley, J. L.,Levy, D. E.,Rimm, E. B.,Gelsomin, E. D.,Anderson, E. M.,Sanford, J. M.,Thorndike, A. N. Association of Worksite Food Purchases and Employees’ Overall Dietary Quality and Health. Am J Prev Med. 2019; 57 (1):87-94. doi: 10.1016/j.amepre.2019.02.020. | Intervention/Exposure
95 | McDaniel, J. C.,Belury, M. A. Are young adults following the dietary guidelines for Americans?. Nurse Pract. 2012; 37 (5):1-9. doi: 10.1097/01.NPR.0000413484.90121.d8. | Outcome
96 | McDermott, A. J.,Stephens, M. B. Cost of eating: whole foods versus convenience foods in a low-income model. Fam Med. 2010; 42 (4):280-4. | Outcome
97 | Middaugh, A. L.,Fisk, P. S.,Brunt, A.,Rhee, Y. S. Few Associations between Income and Fruit and Vegetable Consumption. Journal of Nutrition Education and Behavior. 2012; 44 (3):196-203. doi: 10.1016/j.jneb.2011.10.003. | Intervention/Exposure, Outcome
98 | Molitor, F.,Doerr, C.,Pugliese, J.,Whetstone, L. Three-year trends in dietary behaviours among mothers, teenagers and children from SNAP-Ed (Supplemental Nutrition Assistance Program-Education) eligible households across California. Public Health Nutr. 2020; 23 (1):3-12. doi: 10.1017/S1368980019003197. | Intervention/Exposure
99 | Monsivais, P.,Aggarwal, A.,Drewnowski, A. Following federal guidelines to increase nutrient consumption may lead to higher food costs for consumers. Health Aff (Millwood). 2011; 30 (8):1471-7. doi: 10.1377/hlthaff.2010.1273. | Outcome
100 | Monsivais, P.,Drewnowski, A. Lower-energy-density diets are associated with higher monetary costs per kilocalorie and are consumed by women of higher socioeconomic status. J Am Diet Assoc. 2009; 109 (5):814-22. doi: 10.1016/j.jada.2009.02.002. | Outcome, Data date range
101 | Monsivais, P.,Perrigue, M. M.,Adams, S. L.,Drewnowski, A. Measuring diet cost at the individual level: a comparison of three methods. Eur J Clin Nutr. 2013; 67 (11):1220-5. doi: 10.1038/ejcn.2013.176. | Outcome
102 | Mulik, K.,Haynes-Maslow, L. The Affordability of MyPlate: An Analysis of SNAP Benefits and the Actual Cost of Eating According to the Dietary Guidelines. J Nutr Educ Behav. 2017; 49 (8):623-631 e1. doi: 10.1016/j.jneb.2017.06.005. | Outcome, Multiple food groups
103 | Mulik, Kranti,Haynes Maslow, Lindsey. Is MyPlate really Affordable? An analysis of SNAP Benefits and the actual cost of eating according to the dietary guidelines. . 2016; doi: 10.22004/ag.econ.235924. | Intervention/Exposure, Outcome
104 | Nicklas, T. A.,Jahns, L.,Bogle, M. L.,Chester, D. N.,Giovanni, M.,Klurfeld, D. M.,Laugero, K.,Liu, Y.,Lopez, S.,Tucker, K. L. Barriers and facilitators for consumer adherence to the dietary guidelines for Americans: the HEALTH study. J Acad Nutr Diet. 2013; 113 (10):1317-31. doi: 10.1016/j.jand.2013.05.004. | Outcome
105 | O’Keeffe, M.,Jansen, C.,Martin, L.,Williams, M.,Seamark, L.,Staudacher, H. M.,Irving, P. M.,Whelan, K.,Lomer, M. C. Long-term impact of the low-FODMAP diet on gastrointestinal symptoms, dietary intake, patient acceptability, and healthcare utilization in irritable bowel syndrome. Neurogastroenterol Motil. 2018; 30 (1) doi: 10.1111/nmo.13154. | Intervention/Exposure, Outcome
106 | Parker, H. W.,de Araujo, C.,Thorndike, A. N.,Vadiveloo, M. K. The utility of household Grocery Purchase Quality Index scores as an individual diet quality metric. Br J Nutr. 2020; :1-9. doi: 10.1017/S0007114520004833. | Intervention/Exposure
107 | Parum, Faith,Dharmasena, Senarath. U.S. Consumers’ Intake of Food at Home (FAH) and Food Away from Home (FAFH) As a Complex Economic System. Journal of Food Distribution Research. 2021; 52 (1):77-85. | Outcome
108 | Ranjit, N.,Macias, S.,Hoelscher, D. Factors related to poor diet quality in food insecure populations. Transl Behav Med. 2020; 10 (6):1297-1305. doi: 10.1093/tbm/ibaa028. | Outcome
109 | Rehm, C. D.,Drewnowski, A. Replacing American Breakfast Foods with Ready-To-Eat (RTE) Cereals Increases Consumption of Key Food Groups and Nutrients among US Children and Adults: Results of an NHANES Modeling Study. Nutrients. 2017; 9 (9) doi: 10.3390/nu9091010. | Comparator
110 | Rehm, C. D.,Monsivais, P.,Drewnowski, A. The quality and monetary value of diets consumed by adults in the United States. Am J Clin Nutr. 2011; 94 (5):1333-9. doi: 10.3945/ajcn.111.015560. | Data date range
111 | Richardson, A. S.,Collins, R. L.,Ghosh-Dastidar, B.,Ye, F.,Hunter, G. P.,Baird, M. D.,Schwartz, H.,Sloan, J. C.,Nugroho, A.,Beckman, R.,Troxel, W. M.,Gary-Webb, T. L.,Dubowitz, T. Improvements in Neighborhood Socioeconomic Conditions May Improve Resident Diet. Am J Epidemiol. 2021; 190 (5):798-806. doi: 10.1093/aje/kwaa220. | Intervention/Exposure
112 | Robert Wood Johnson Foundation. Improving the Health of All Americans through Better Nutrition . . nd; | Study design, Pubilcation status
113 | Robinson, Courtney N.,Baker, Gregory A.,Harwood, Michael J.,Diekmann, Lucy O. Food expenditures and consumption by food bank clients in Silicon Valley. International Food & Agribusiness Management Review. 2020; 23 (4):619-632. doi: 10.22434/IFAMR2019.0125. | Outcome
114 | Rogus, S. Examining the influence of perceived and objective time constraints on the quality of household food purchases. Appetite. 2018; 130 :268-273. doi: 10.1016/j.appet.2018.08.025. | Intervention/Exposure
115 | Ryden, P. J.,Hagfors, L. Diet cost, diet quality and socio-economic position: how are they related and what contributes to differences in diet costs?. Public Health Nutrition. 2011; 14 (9):1680-1692. doi: 10.1017/S1368980010003642. | Country
116 | Scharadin, B.,Yu, Y.,Jaenicke, E. C. Household time activities, food waste, and diet quality: the impact of non-marginal changes due to COVID-19. Rev Econ Househ. 2021; :1-30. doi: 10.1007/s11150-021-09555-w. | Intervention/Exposure
117 | Schreiner, N.,Perazzo, J.,Digenarro, S.,Currie, J.,Daly, B.,Webel, A. Examining the Association between Item Specific Treatment Burden and Adherence in People Living with HIV. West J Nurs Res. 2020; 42 (7):495-502. doi: 10.1177/0193945919880317. | Intervention/Exposure
118 | Sheldon, M.,Gans, K. M.,Tai, R.,George, T.,Lawson, E.,Pearlman, D. N. Availability, affordability, and accessibility of a healthful diet in a low-income community, Central Falls, Rhode Island, 2007-2008. Prev Chronic Dis. 2010; 7 (2):A43. | Outcome
119 | Silver, L. D.,Ng, S. W.,Ryan-Ibarra, S.,Taillie, L. S.,Induni, M.,Miles, D. R.,Poti, J. M.,Popkin, B. M. Changes in prices, sales, consumer spending, and beverage consumption one year after a tax on sugar-sweetened beverages in Berkeley, California, US: A before-and-after study. PLoS Med. 2017; 14 (4):e1002283. doi: 10.1371/journal.pmed.1002283. | Outcome
120 | Smith, T. A.,Valizadeh, P.,Lin, B. H.,Coats, E. What is driving increases in dietary quality in the United States?. Food Policy. 2019; 86 doi: 10.1016/j.foodpol.2019.05.003. | Intervention/Exposure
121 | Sogari, Giovanni,Velez-Argumedo, Catalina,Gómez, Miguel I.,Mora, Cristina. College Students and Eating Habits: A Study Using An Ecological Model for Healthy Behavior. . 2019; doi: 10.22004/ag.econ.300040. | Outcome
122 | Sturm, R.,Datar, A. Regional price differences and food consumption frequency among elementary school children. Public Health. 2011; 125 (3):136-41. doi: 10.1016/j.puhe.2010.11.016. | Outcome
123 | Surkan, P. J.,Coutinho, A. J.,Christiansen, K.,Dennisuk, L. A.,Suratkar, S.,Mead, E.,Sharma, S.,Gittelsohn, J. Healthy food purchasing among African American youth: associations with child gender, adult caregiver characteristics and the home food environment. Public Health Nutrition. 2011; 14 (4):670-677. doi: 10.1017/S136898001000251X. | Outcome
124 | Tiwari, A.,Aggarwal, A.,Tang, W.,Drewnowski, A. Cooking at Home: A Strategy to Comply With U.S. Dietary Guidelines at No Extra Cost. Am J Prev Med. 2017; 52 (5):616-624. doi: 10.1016/j.amepre.2017.01.017. | Comparator
125 | Tran, L. T.,Brewster, P. J.,Chidambaram, V.,Hurdle, J. F. Towards Measuring the Food Quality of Grocery Purchases: an Estimation Model of the Healthy Eating Index-2010 Using only Food Item Counts. Procedia Food Sci. 2015; 4 :148-159. doi: 10.1016/j.profoo.2015.06.020. | Intervention/Exposure
126 | Vadiveloo, M. K.,Parker, H. W.,Juul, F.,Parekh, N. Sociodemographic Differences in the Dietary Quality of Food-at-Home Acquisitions and Purchases among Participants in the U.S. Nationally Representative Food Acquisition and Purchase Survey (FoodAPS). Nutrients. 2020; 12 (8) doi: 10.3390/nu12082354. | Intervention/Exposure
127 | Vadiveloo, M.,Guan, X.,Parker, H. W.,Perraud, E.,Buchanan, A.,Atlas, S.,Thorndike, A. N. Effect of Personalized Incentives on Dietary Quality of Groceries Purchased: A Randomized Crossover Trial. JAMA Netw Open. 2021; 4 (2):e2030921. doi: 10.1001/jamanetworkopen.2020.30921. | Intervention/Exposure, Outcome
128 | Vadiveloo, M.,Perraud, E.,Parker, H. W.,Juul, F.,Parekh, N. Geographic Differences in the Dietary Quality of Food Purchases among Participants in the Nationally Representative Food Acquisition and Purchase Survey (FoodAPS). Nutrients. 2019; 11 (6) doi: 10.3390/nu11061233. | Intervention/Exposure
129 | Vilaro, M. J.,Barnett, T. E.,Mathews, A.,Pomeranz, J.,Curbow, B. Income differences in social control of eating behaviors and food choice priorities among southern rural women in the US: A qualitative study. Appetite. 2016; 107 :604-612. doi: 10.1016/j.appet.2016.09.003. | Outcome
130 | Vogel, C.,Ntani, G.,Inskip, H.,Barker, M.,Cummins, S.,Cooper, C.,Moon, G.,Baird, J. Education and the Relationship Between Supermarket Environment and Diet. Am J Prev Med. 2016; 51 (2):e27-e34. doi: 10.1016/j.amepre.2016.02.030. | Country
131 | Volpe, Richard,Cai, Xiaowei,Schroeter, Christiane,Mancino, Lisa. Adherence to Dietary Recommendations and Food Retail Market Structure: Is There a Connection?. Journal of Agricultural & Food Industrial Organization. 2020; :1. doi: 10.1515/jafio-2019-0035. | Outcome
132 | Wang, M.,Levi, R.,Seligman, H. New SNAP Eligibility in California Associated With Improved Food Security and Health. Prev Chronic Dis. 2021; 18 :E28. doi: 10.5888/pcd18.200587. | Intervention/Exposure, Outcome
133 | Weatherspoon, D. D.,Miller, S. R.,Steele, M. E.,Newkirk, C. J.,Santiago, O.,Dembele, A. S.,Hoerr, S. L. What Social, Program, and Behavioral Factors Influence the Healthy Eating Index for EFNEP and SNAP-Ed Adult Participants?. Am J Lifestyle Med. 2017; 11 (4):344-353. doi: 10.1177/1559827615607194. | Intervention/Exposure
134 | Whiteman, E. D.,Chrisinger, B. W.,Hillier, A. Diet Quality Over the Monthly Supplemental Nutrition Assistance Program Cycle. Am J Prev Med. 2018; 55 (2):205-212. doi: 10.1016/j.amepre.2018.04.027. | Intervention/Exposure, Outcome
135 | Wilcox, S.,Sharpe, P. A.,Liese, A. D.,Dunn, C. G.,Hutto, B. Socioeconomic factors associated with diet quality and meeting dietary guidelines in disadvantaged neighborhoods in the Southeast United States. Ethn Health. 2020; 25 (8):1115-1131. doi: 10.1080/13557858.2018.1493434. | Intervention/Exposure
136 | Wilde, Parke E.,Llobrera, Joseph. Using the Thrifty Food Plan to Assess the Cost of a Nutritious Diet. Journal of Consumer Affairs. 2009; 43 (2):274-304. doi: 10.1111/j.1745-6606.2009.01140.x. | Outcome
137 | Willits-Smith, A.,Aranda, R.,Heller, M. C.,Rose, D. Addressing the carbon footprint, healthfulness, and costs of self-selected diets in the USA: a population-based cross-sectional study. Lancet Planet Health. 2020; 4 (3):e98-e106. doi: 10.1016/S2542-5196(20)30055-3. | Intervention/Exposure
138 | You, W.,Zhang, G.,Davy, B. M.,Carlson, A.,Lin, B. H. Food consumed away from home can be a part of a healthy and affordable diet. J Nutr. 2009; 139 (10):1994-9. doi: 10.3945/jn.109.107615. | Data date range
139 | Young, C. M.,Batch, B. C.,Svetkey, L. P. Effect of socioeconomic status on food availability and cost of the Dietary Approaches to Stop Hypertension (DASH) dietary pattern. J Clin Hypertens (Greenwich). 2008; 10 (8):603-11. doi: 10.1111/j.1751-7176.2008.08199.x. | Outcome, Multiple food groups