# Appendix 3-a Literature search strategy for the rapid review on diet cost and HEI

Database: PubMed

Vendor: National Library of Medicine

Date of Search: June 18, 2021

Limits Used: Filters: Language English; Publication Dates 2008 - 2021

Total = 1,152

Search # | Concept | Search String | N
#1 | Diet | “Food and Beverages”[Mesh] OR food*[tiab] OR “Diet, Healthy”[Mesh] OR “healthy diet*”[tiab] OR “unhealthy diet*”[tiab] OR diet[tiab] | 1,283,793
#2 | Price/Cost | “Costs and Cost Analysis”[Mesh] OR cost*[tiab] OR price*[tiab] OR pricing*[tiab] OR affordab*[tiab] OR expense*[tiab] OR expenditure*[tiab] OR budget*[tiab] OR purchas*[tiab] OR cash[tiab] OR money[tiab] OR monetary[tiab] OR monies[tiab] | 945,938
#3 | HEI (including dietary patterns terms) | HEI OR “healthy eating index” OR “diet quality”[tiab] OR “dietary quality”[tiab] OR “dietary guidelines” OR “dietary recommendation*”[tiab] OR “dietary intake*”[tiab] OR “dietary consumption”[tiab] OR “eating style*”[tiab] OR “Guideline Adherence”[Mesh] OR “guideline adherence*”[tiab] OR “diet score*”[tiab] OR “diet quality score*”[tiab] OR “diet quality index*”[tiab] OR “diet index*”[tiab] OR “dietary index*”[tiab] OR “food score*”[tiab] OR “dietary pattern*”[tiab] OR “diet pattern*”[tiab] OR “eating pattern*”[tiab] OR “food pattern*”[tiab] | 88,968
#4 | | #1 AND #2 AND #3 | 3,188
#5 | Non-United States | #1 AND #2 AND #3 NOT (“Developing Countries”[Mesh] OR “developing countr*” OR “Under Developed Nation*” OR “low income countr*” OR “middle income countr*”OR “low-middle-income countr*” OR LMIC[tiab] OR “Europe”[Mesh] OR “Australia”[Mesh] OR “Asia”[Mesh] OR “Africa”[Mesh] OR “Mexico”[Mesh] OR “Islands”[Mesh] OR “Central America”[Mesh] OR “Latin America”[Mesh] OR “South America”[Mesh]) | 2,146
#6 | Publication Excludes | NOT (letter[ptyp] OR editorial[ptyp] OR comment[ptyp] OR news[ptyp] OR “Congress”[Publication Type] OR “Consensus Development Conference”[Publication Type] OR editorial[tiab] OR commentary[tiab] OR “conference abstract*”[tiab] OR “systematic review*”[ti] OR “meta-analysis”[ptyp] OR “meta-analysis”[ti] OR “meta-analyses”[ti] OR “Review”[Publication Type] OR “Systematic Review”[Publication Type] OR “conference proceeding*”[tiab] OR “retracted publication”[ptyp] OR “retraction of publication”[ptyp] OR “retraction of publication”[tiab] OR “retraction notice”[ti] OR “retracted publication”[tiab] OR “Published Erratum”[Publication Type] OR corrigenda[tiab] OR corrigendum[tiab] OR errata[tiab] OR erratum[tiab] OR protocol[ti] OR protocols[ti] OR “case report”[ti] OR “case series”[ti] OR “Case Reports” [Publication Type]) | 1,657
#7 | Animal Excludes | NOT (“Animals”[Mesh] NOT (“Animals”[Mesh] AND “Humans”[Mesh])) | 1,562
#8 | Limits: Language/Dates | Filters: English, from 2008 - 2021 | 1,152

Database: Business Source Premier

Vendor: EBSCO

Date of Search: June 18, 2021

Limits Used: Scholarly (Peer Reviewed) Journals; Published Date: 20080101-20211231; Document Type: Article; Language: English

Total = 887

Search # | Concept | Search String | N
#1 | Diet | (DE “BEVERAGE consumption”) OR (DE “FOOD consumption forecasting”) OR (DE “FOOD consumption statistics”) OR food* OR “healthy diet*” OR “unhealthy diet*” | 704,148
#2 | Price/Cost | (DE “FOOD prices”) OR cost* OR price* OR pricing OR affordab* OR expense* OR expenditure* OR budget* OR purchas* OR cash OR money OR monetary OR monies | 3,680,852
#3 | HEI (including dietary patterns terms) | HEI OR “healthy eating index” OR “diet quality” OR “dietary quality” OR “dietary guidelines” OR “dietary recommendation*” OR “dietary intake*” OR “dietary consumption” OR “eating style*” OR “guideline adherence*” OR “diet score*” OR “diet quality score*” OR “diet quality index*” OR “diet index*” OR “dietary index*” OR “food score*” OR “dietary pattern*” OR “diet pattern*” OR “eating pattern*” OR “food pattern*” | 11,319
#4 | | #1 AND #2 AND #3 | 2,269
#5 | Filters | Limiters - Scholarly (Peer Reviewed) Journals; Published Date: 20080101-20211231; Document Type: Article; Language: English | 887

Database: Web of Science: Core Collection

Vendor: Clarivate Analytics

Date of Search: 6/18/2021

Limits Used: Years: 2008-2021; Publication Types: Articles, Early Access; Language: English

Total = 2,022

Search # | Concept | Search String | N
#1 | Diet | (TS=(food* OR “healthy diet*” OR “unhealthy diet*”) ) | 824,277
#2 | Price/Cost | (TS=(cost* OR price* OR affordab* OR expense* OR expenditure* OR budget* OR purchas* OR cash OR money OR monetary OR monies ) ) | 1,873,881
#3 | HEI | (TS=( HEI OR “healthy eating index” OR “diet quality” OR “dietary quality” OR “dietary guidelines” OR “dietary recommendation*” OR “dietary intake*” OR “dietary consumption” OR “eating style*” OR “guideline adherence*” OR “diet score*” OR “diet quality score*” OR “diet quality index*” OR “diet index*” OR “dietary index*” OR “food score*” OR “dietary pattern*” OR “diet pattern*” OR “eating pattern*” OR “food pattern*”)) | 64,270
#4 | #1 AND #2 AND #3 | | 3,559
#5 | Non-United States Excludes | CU=(“developing countr*” OR “under developed nation*” OR “low income countr*” OR “middle income; countr*” OR “low-middle income countr*” OR LMIC; OR Europe OR Australia OR Asia OR Africa OR Mexico OR Islands OR “Central America” OR “Latin America” OR “South America”) | 2,061,484
#6 | #4 NOT #5 | | 3,137
#7 | Publication Excludes | TS=(editorial OR commentary OR “conference abstract*” OR “conference proceeding*”[tiab] OR “retraction of publication” OR “retracted publication” OR corrigenda[tiab] OR corrigendum[tiab] OR errat a OR erratum OR “case reports” ) OR TI=(“systematic review*” OR “meta-analysis”; OR “meta analyses” OR protocol OR protocols; OR “retraction notice” OR “case report” OR; “case series”) | 721,284
#8 | #6 NOT #7 | | 3,054
#9 | | Years: 2008-2021; Publication Types: Articles, Early Access; Language: English | 2,022

## Grey Literature Search

### Google Scholar

(Food OR diet) AND (Price OR cost OR budget OR money) AND (HEI OR “healthy eating index” OR dietary)

Limits: Date Published: 2008-2021;

Date Searched: 6/18/2021

Results: 50, limited to 5 pages

### Google

site:.gov AND (diet OR food) AND (cost OR price) AND “healthy eating index”

Limits:

Date Searched: 6/18/2021

Results: Date Published: 30, limited to 3 pages

### AgEcon

Any of the words: food diet

AND

Any of the words: cost price

AND

Any of the words: HEI “healthy eating index” dietary

Limits: Added/Modified since: 2008;

Date Searched: 6/21/2021

Results: Date Published: 40, limited to 4 pages