# Appendix 2-b Excluded articles for the rapid review on income and HEI

The following table lists the articles excluded after full-text screening for this rapid review question. At least 1 reason for exclusion is provided for each article, though this may not reflect all possible reasons. Information about articles excluded after title and abstract screening is available upon request.

# | Citation | Exclusion rationale
1 | . Access to Foods that Support Healthy Eating Patterns \| Healthy People 2020. 2021. | Study design
2 | . Appendix E-2.37 \| health.gov. 2021. | Study design
3 | . Eating Vegetarian \| Nutrition.gov. 2021. | Study design
4 | . Food Pattern Modeling \| Dietary Guidelines for Americans. 2021. | Study design; Publication Status
5 | . Multicultural Healthy Diet to Reduce Cognitive Decline & Alzheimer’s Disease Risk \| National Institute on Aging. 2021. | Study design; Publication Status
6 | . Promote Healthy Diet and Physical Activity Behavior \| Performance.gov. 2021. | Study design
7 | . The Mediterranean Eating Plan \| Evidence-Based Cancer Control Programs (EBCCP). 2021. | Study design
8 | . USDA ERS - Diet Quality & Nutrition. 2021. | Study design
9 | . Vegetarian Diet. 2021. | Intervention/Exposure; Study design
10 | . Vegetarian Nutrition \| Food and Nutrition Information Center \| NAL \| USDA. 2021. | Study design
11 | Aggarwal, A.,Drewnowski, A.. Plant- and animal-protein diets in relation to sociodemographic drivers, quality, and cost: findings from the Seattle Obesity Study. Am J Clin Nutr. 2019. 110:451-460 | Intervention/Exposure
12 | Aggarwal, A.,Monsivais, P.,Cook, A. J.,Drewnowski, A.. Does diet cost mediate the relation between socioeconomic position and diet quality?. Eur J Clin Nutr. 2011. 65:1059-66 | Outcome
13 | Alexis, T. D.,Unruh, D.,Wang, W.,Dave, J. M.,Miketinas, D. C.,Chen, T. A.,Moore, C. E.. Implementation of a food scholarship program improves nutrient intake and dietary quality of college students. J Am Coll Health. 2020. :1-8 | Intervention/Exposure
14 | Anderson, S. E.,Kaye, G.,Andridge, R.,Smathers, C.,Peng, J.,Pirie, P.. Interrelationships of More Healthful and Less Healthful Aspects of Diet Quality in a Low-Income Community Sample of Preschool-Aged Children. Matern Child Health J. 2015. 19:2663-72 | Intervention/Exposure
15 | Anderson, S. E.,Ramsden, M.,Kaye, G.. Diet qualities: healthy and unhealthy aspects of diet quality in preschool children. Am J Clin Nutr. 2016. 103:1507-13 | Data date range
16 | Andreyeva, T.,Tripp, A. S.. The healthfulness of food and beverage purchases after the federal food package revisions: The case of two New England states. Prev Med. 2016. 91:204-210 | Outcome
17 | Appelhans, B. M.,French, S. A.,Tangney, C. C.,Powell, L. M.,Wang, Y.. To what extent do food purchases reflect shoppers’ diet quality and nutrient intake?. Int J Behav Nutr Phys Act. 2017; 14 (1):46. | Outcome
18 | Arimond, Mary ,Wiesmann, Doris,Becquey, Elodie ,Carriquiry, Alicia ,Daniels, Melissa ,Deitchler, Megan ,Fanou, Nadia,Ferguson, Elaine ,Joseph, Maria ,Kennedy, Gina ,Martin-Prével, Yves ,Elin Torheim, Liv . Dietary Diversity as a Measure of the Micronutrient Adequacy of Women’s Diets in Resource-Poor Areas: Summary of Results from Five Sites. 2011. | Country
19 | Auchincloss, A. H.,Riolo, R. L.,Brown, D. G.,Cook, J.,Diez Roux, A. V.. An agent-based model of income inequalities in diet in the context of residential segregation. Am J Prev Med. 2011. 40:303-11 | Outcome
20 | Baraldi, L. G.,Martinez Steele, E.,Canella, D. S.,Monteiro, C. A.. Consumption of ultra-processed foods and associated sociodemographic factors in the USA between 2007 and 2012: evidence from a nationally representative cross-sectional study. BMJ Open. 2018. 8:e020574 | Outcome
21 | Basu, S.,Gardner, C. D.,White, J. S.,Rigdon, J.,Carroll, M. M.,Akers, M.,Seligman, H. K.. Effects Of Alternative Food Voucher Delivery Strategies On Nutrition Among Low-Income Adults. Health Aff (Millwood). 2019. 38:577-584 | Intervention/Exposure
22 | Bauer, K. W.,Widome, R.,Himes, J. H.,Smyth, M.,Rock, B. H.,Hannan, P. J.,Story, M.. High food insecurity and its correlates among families living on a rural American Indian Reservation. Am J Public Health. 2012. 102:1346-52 | Data date range
23 | Beasley, J. M.,Sevick, M. A.,Kirshner, L.,Mangold, M.,Chodosh, J.. Congregate Meals: Opportunities to Help Vulnerable Older Adults Achieve Diet and Physical Activity Recommendations. J Frailty Aging. 2018. 7:182-186 | Outcome
24 | Bedrick, B. S.,Eskew, A. M.,Chavarro, J. E.,Jungheim, E. S.. Dietary Patterns, Physical Activity, and Socioeconomic Associations in a Midwestern Cohort of Healthy Reproductive-Age Women. Matern Child Health J. 2020. 24:1299-1307 | Intervention/Exposure
25 | Bergmans, R. S.,Palta, M.,Robert, S. A.,Berger, L. M.,Ehrenthal, D. B.,Malecki, K. M.. Associations between Food Security Status and Dietary Inflammatory Potential within Lower-Income Adults from the United States National Health and Nutrition Examination Survey, Cycles 2007 to 2014. Journal of the Academy of Nutrition and Dietetics. 2018. 118:994-1005 | Intervention/Exposure
26 | Bernstein, A. M.,Bloom, D. E.,Rosner, B. A.,Franz, M.,Willett, W. C.. Relation of food cost to healthfulness of diet among US women. American Journal of Clinical Nutrition. 2010. 92:1197-1203 | Data date range
27 | Beydoun, M. A.,Wang, Y.. Do nutrition knowledge and beliefs modify the association of socio-economic factors and diet quality among US adults?. Prev Med. 2008. 46:145-53 | Data date range
28 | Beydoun, M. A.,Wang, Y.. How do socio-economic status, perceived economic barriers and nutritional benefits affect quality of dietary intake among US adults?. Eur J Clin Nutr. 2008. 62:303-13 | Data date range
29 | Bishop, N. J.,Zuniga, K. E.,Ramirez, C. M.. Latent profile analysis of dietary intake in a community-dwelling sample of older Americans. Public Health Nutr. 2020. 23:243-253 | Outcome
30 | Blake, C. E.,Wethington, E.,Farrell, T. J.,Bisogni, C. A.,Devine, C. M.. Behavioral contexts, food-choice coping strategies, and dietary quality of a multiethnic sample of employed parents. J Am Diet Assoc. 2011. 111:401-7 | Intervention/Exposure; Data date range
31 | Bleiweiss-Sande, R.,Sacheck, J. M.,Chui, K.,Goldberg, J. P.,Bailey, C.,Evans, E. W.. Processed food consumption is associated with diet quality, but not weight status, in a sample of low-income and ethnically diverse elementary school children. Appetite. 2020. 151:104696 | Comparator
32 | Bodnar, L. M.,Simhan, H. N.,Parker, C. B.,Meier, H.,Mercer, B. M.,Grobman, W. A.,Haas, D. M.,Wing, D. A.,Hoffman, M. K.,Parry, S.,Silver, R. M.,Saade, G. R.,Wapner, R.,Iams, J. D.,Wadhwa, P. D.,Elovitz, M.,Peaceman, A. M.,Esplin, S.,Barnes, S.,Reddy, U. M.. Racial or Ethnic and Socioeconomic Inequalities in Adherence to National Dietary Guidance in a Large Cohort of US Pregnant Women. J Acad Nutr Diet. 2017. 117:867-877.e3 | Intervention/Exposure
33 | Boehm, R.,Ver Ploeg, M.,Wilde, P. E.,Cash, S. B.. Greenhouse gas emissions, total food spending and diet quality by share of household food spending on red meat: results from a nationally representative sample of US households. Public Health Nutr. 2019. 22:1794-1806 | Intervention/Exposure
34 | Boone-Heinonen, J.,Gordon-Larsen, P.,Kiefe, C. I.,Shikany, J. M.,Lewis, C. E.,Popkin, B. M.. Fast food restaurants and food stores: longitudinal associations with diet in young to middle-aged adults: the CARDIA study. Arch Intern Med. 2011. 171:1162-70 | Data date range
35 | Bottino, C. J.,Fleegler, E. W.,Cox, J. E.,Rhodes, E. T.. The Relationship Between Housing Instability and Poor Diet Quality Among Urban Families. Acad Pediatr. 2019. 19:891-898 | Intervention/Exposure
36 | Boutté, A. K.,Turner-McGrievy, G. M.,Eberth, J. M.,Wilcox, S.,Liu, J.,Kaczynski, A. T.. Healthy Food Density is Not Associated With Diet Quality Among Pregnant Women With Overweight/Obesity in South Carolina. J Nutr Educ Behav. 2021. 53:120-129 | Intervention/Exposure
37 | Boynton, A.,Neuhouser, M. L.,Sorensen, B.,McTiernan, A.,Ulrich, C. M.. Predictors of diet quality among overweight and obese postmenopausal women. J Am Diet Assoc. 2008. 108:125-30 | Data date range
38 | Brantley, K. D.,Hartman, T. J.,Patel, A. V.,Gapstur, S. M.,Flanders, W. D.,McCullough, M. L.. Test-Retest Reproducibility of Adult-Reported High School Diet Varies among Racially and Ethnically Diverse US Men and Women. J Nutr. 2018. 148:599-606 | Intervention/Exposure
39 | Brewster, P. J.,Durward, C. M.,Hurdle, J. F.,Stoddard, G. J.,Guenther, P. M.. The Grocery Purchase Quality Index-2016 Performs Similarly to the Healthy Eating Index-2015 in a National Survey of Household Food Purchases. J Acad Nutr Diet. 2019. 119:45-56 | Outcome (Purchase data)
40 | Bruening, M.,McClain, D.,Moramarco, M.,Reifsnider, E.. The Role of SNAP in Home Food Availability and Dietary Intake among WIC Participants Facing Unstable Housing. Public Health Nurs. 2017. 34:219-228 | Outcome
41 | Bruening, M.,van Woerden, I.,Todd, M.,Laska, M. N.. Hungry to learn: the prevalence and effects of food insecurity on health behaviors and outcomes over time among a diverse sample of university freshmen. Int J Behav Nutr Phys Act. 2018. 15:9 | Outcome
42 | Camacho-Rivera, M.,Rosenbaum, E.,Yama, C.,Chambers, E.. Low-Income Housing Rental Assistance, Perceptions of Neighborhood Food Environment, and Dietary Patterns among Latino Adults: the AHOME Study. J Racial Ethn Health Disparities. 2017. 4:346-353 | Outcome
43 | Campbell, S.,Chen, J. J.,Boushey, C. J.,Eicher-Miller, H.,Zhu, F. Q.,Fialkowski, M. K.. Food Security and Diet Quality in Native Hawaiian, Pacific Islander, and Filipino Infants 3 to 12 Months of Age. Nutrients. 2020. 12:18 | Intervention/Exposure
44 | Cantor, J.,Beckman, R.,Collins, R. L.,Dastidar, M. G.,Richardson, A. S.,Dubowitz, T.. SNAP Participants Improved Food Security And Diet After A Full-Service Supermarket Opened In An Urban Food Desert. Health Aff (Millwood). 2020. 39:1386-1394 | Intervention/Exposure
45 | Caspi, C. E.,Lenk, K.,Pelletier, J. E.,Barnes, T. L.,Harnack, L.,Erickson, D. J.,Laska, M. N.. Association between store food environment and customer purchases in small grocery stores, gas-marts, pharmacies and dollar stores. Int J Behav Nutr Phys Act. 2017. 14:76 | Intervention/Exposure
46 | Caspi, C. E.,Lenk, K.,Pelletier, J. E.,Barnes, T. L.,Harnack, L.,Erickson, D. J.,Laska, M. N.. Food and beverage purchases in corner stores, gas-marts, pharmacies and dollar stores. Public Health Nutr. 2017. 20:2587-2597 | Intervention/Exposure
47 | Chang, Y.,Hickman, H.. Food Insecurity and Perceived Diet Quality Among Low-Income Older Americans with Functional Limitations. J Nutr Educ Behav. 2018. 50:476-484 | Intervention/Exposure
48 | Chen, L.,Zhu, H.,Gutin, B.,Dong, Y.. Race, Gender, Family Structure, Socioeconomic Status, Dietary Patterns, and Cardiovascular Health in Adolescents. Curr Dev Nutr. 2019. 3:nzz117 | Intervention/Exposure
49 | Chen, M.,Creger, T.,Howard, V.,Judd, S. E.,Harrington, K. F.,Fontaine, K. R.. Geospatial analysis of Mediterranean diet adherence in the United States. Public Health Nutr. 2020. :1-9 | Intervention/Exposure
50 | Chen, Y.,Lin, B. H.,Mancino, L.,Ploeg, M. V.,Zhen, C.. Nutritional quality of retail food purchases is not associated with participation in the Supplemental Nutrition Assistance Program for nutrition-oriented households. Plos One. 2020. 15:14 | Outcome (Purchase data)
51 | Chenarides, Lauren,Grebitus, Carola,Lusk, Jayson L.,Printezis, Iryna. Food consumption behavior during the COVID-19 pandemic. Agribusiness. 2021. 37:44-81 | Intervention/Exposure; Outcome
52 | Cleary, Rebecca,Bonanno, Alessandro,Ghazaryan, Armen,Bellows, Laura,McCloskey, Morgan. School meals and quality of household food acquisitions. Applied Economic Perspectives & Policy. 2021; (#issue#):1. #doi#. | Outcome (Purchase data)
53 | Clements, Kenneth W.,Si, Jiawei. ENGEL’S LAW, DIET DIVERSITY, AND THE QUALITY OF FOOD CONSUMPTION. American Journal of Agricultural Economics. 2018. 100:1-22 | Study design; Country
54 | Collins, A. M.,Klerman, J. A.. Improving Nutrition by Increasing Supplemental Nutrition Assistance Program Benefits. Am J Prev Med. 2017. 52:S179-s185 | Outcome
55 | Cooksey Stowers, K.,Jiang, Q.,Atoloye, A.,Lucan, S.,Gans, K.. Racial Differences in Perceived Food Swamp and Food Desert Exposure and Disparities in Self-Reported Dietary Habits. Int J Environ Res Public Health. 2020. 17: | Outcome
56 | Côté-Lussier, C.,Kakinami, L.,Danieles, P. K.. Ego-centered relative neighborhood deprivation and reported dietary habits among youth. Appetite. 2019. 132:267-274 | Country
57 | Courtemanche, Charles,Denteh, Augustine,Tchernis, Rusty. Estimating the Associations between SNAP and Food Insecurity, Obesity, and Food Purchases with Imperfect Administrative Measures of Participation. Southern Economic Journal. 2019. 86:202-228 | Comparator
58 | Crane, M. M.,Tangney, C. C.,French, S. A.,Wang, Y.,Appelhans, B. M.. Gender Comparison of the Diet Quality and Sources of Food Purchases Made by Urban Primary Household Food Purchasers. J Nutr Educ Behav. 2019. 51:199-204 | Intervention/Exposure
59 | Crews, D. C.,Kuczmarski, M. F.,Miller, E. R., 3rd,Zonderman, A. B.,Evans, M. K.,Powe, N. R.. Dietary habits, poverty, and chronic kidney disease in an urban population. J Ren Nutr. 2015. 25:103-10 | Outcome
60 | Cullen, K. W.,Chen, T. A.. The contribution of the USDA school breakfast and lunch program meals to student daily dietary intake. Prev Med Rep. 2017. 5:82-85 | Intervention/Exposure; Outcome
61 | Cummins, Steven,Flint, Ellen,Matthews, Stephen A.. New Neighborhood Grocery Store Increased Awareness Of Food Access But Did Not Alter Dietary Habits Or Obesity. Health Affairs. 2014. 33:283-291 | Outcome
62 | Cutler, G. J.,Flood, A.,Hannan, P.,Neumark-Sztainer, D.. Multiple sociodemographic and socioenvironmental characteristics are correlated with major patterns of dietary intake in adolescents. J Am Diet Assoc. 2011. 111:230-40 | Data date range
63 | Dammann, K. W.,Smith, C.. Race, Homelessness, and Other Environmental Factors Associated with the Food-Purchasing Behavior of Low-Income Women. Journal of the American Dietetic Association. 2010. 110:1351-1356 | Outcome
64 | Darmon, N.,Lacroix, A.,Muller, L.,Ruffieux, B.. Food price policies improve diet quality while increasing socioeconomic inequalities in nutrition. Int J Behav Nutr Phys Act. 2014. 11:66 | Country
65 | Darmon, N.,Lacroix, A.,Muller, L.,Ruffieux, B.. Food Price Policies May Improve Diet but Increase Socioeconomic Inequalities in Nutrition. Hidden Hunger: Malnutrition and the First 1,000 Days of Life: Causes, Consequences and Solutions. 2016. 115:36-45 | Country
66 | Davis, N. J.,Schechter, C. B.,Ortega, F.,Rosen, R.,Wylie-Rosett, J.,Walker, E. A.. Dietary patterns in Blacks and Hispanics with diagnosed diabetes in New York City’s South Bronx. Am J Clin Nutr. 2013. 97:878-85 | Outcome
67 | Dennisuk, L. A.,Coutinho, A. J.,Suratkar, S.,Surkan, P. J.,Christiansen, K.,Riley, M.,Anliker, J. A.,Sharma, S.,Gittelsohn, J.. Food expenditures and food purchasing among low-income, urban, African-American youth. Am J Prev Med. 2011. 40:625-8 | Outcome
68 | Deshmukh-Taskar, P. R.,O’Neil, C. E.,Nicklas, T. A.,Yang, S. J.,Liu, Y.,Gustat, J.,Berenson, G. S.. Dietary patterns associated with metabolic syndrome, sociodemographic and lifestyle factors in young adults: the Bogalusa Heart Study. Public Health Nutr. 2009. 12:2493-503 | Data date range
69 | Dhakal, C. K.,Khadka, S.. Heterogeneities in Consumer Diet Quality and Health Outcomes of Consumers by Store Choice and Income. Nutrients. 2021. 13 | Outcome (Purchase data)
70 | Dharod, J. M.,Croom, J. E.,Sady, C. G.. Food Insecurity: Its Relationship to Dietary Intake and Body Weight among Somali Refugee Women in the United States. Journal of Nutrition Education and Behavior. 2013. 45:47-53 | Outcome
71 | Diep, C. S.,Leung, R.,Thompson, D. I.,Gor, B. J.,Baranowski, T.. Culture and Diet Among Chinese American Children Aged 9-13 Years: A Qualitative Study. Journal of Nutrition Education and Behavior. 2017. 49:275-284 | Outcome
72 | Dondero, M.,Van Hook, J.. Generational status, neighborhood context, and mother-child resemblance in dietary quality in Mexican-origin families. Soc Sci Med. 2016. 150:212-20 | Intervention/Exposure
73 | Dubowitz, T.,Ghosh-Dastidar, M.,Cohen, D. A.,Beckman, R.,Steiner, E. D.,Hunter, G. P.,Flórez, K. R.,Huang, C.,Vaughan, C. A.,Sloan, J. C.,Zenk, S. N.,Cummins, S.,Collins, R. L.. Diet And Perceptions Change With Supermarket Introduction In A Food Desert, But Not Because Of Supermarket Use. Health Aff (Millwood). 2015. 34:1858-68 | Intervention/Exposure
74 | Dubowitz, T.,Zenk, S. N.,Ghosh-Dastidar, B.,Cohen, D. A.,Beckman, R.,Hunter, G.,Steiner, E. D.,Collins, R. L.. Healthy food access for urban food desert residents: examination of the food environment, food purchasing practices, diet and BMI. Public Health Nutr. 2015. 18:2220-30 | Intervention/Exposure
75 | Duffy, P.,Zizza, C.,Jacoby, J.,Tayie, F. A.. Diet quality is low among female food pantry clients in Eastern Alabama. J Nutr Educ Behav. 2009. 41:414-9 | Data date range
76 | Egeland, G. M.,Williamson-Bathory, L.,Johnson-Down, L.,Sobol, I.. Traditional food and monetary access to market-food: correlates of food insecurity among Inuit preschoolers. Int J Circumpolar Health. 2011. 70:373-83 | Country
77 | Eicher-Miller, H. A.,Boushey, C. J.,Bailey, R. L.,Yang, Y. J.. Frequently Consumed Foods and Energy Contributions among Food Secure and Insecure U.S. Children and Adolescents. Nutrients. 2020. 12 | Outcome
78 | Eicher-Miller, H. A.,Fulgoni, V. L., 3rd,Keast, D. R.. Energy and Nutrient Intakes from Processed Foods Differ by Sex, Income Status, and Race/Ethnicity of US Adults. J Acad Nutr Diet. 2015. 115:907-18.e6 | Outcome
79 | Eicher-Miller, H. A.,Khanna, N.,Boushey, C. J.,Gelfand, S. B.,Delp, E. J.. Temporal Dietary Patterns Derived among the Adult Participants of the National Health and Nutrition Examination Survey 1999-2004 Are Associated with Diet Quality. J Acad Nutr Diet. 2016. 116:283-91 | Data date range
80 | Epstein, L. H.,Finkelstein, E.,Raynor, H.,Nederkoorn, C.,Fletcher, K. D.,Jankowiak, N.,Paluch, R. A.. Experimental analysis of the effect of taxes and subsides on calories purchased in an on-line supermarket. Appetite. 2015. 95:245-51 | Intervention/Exposure
81 | Ervin, R. B.. Healthy Eating Index scores among adults, 60 years of age and over, by sociodemographic and health characteristics: United States, 1999-2002. Adv Data. 2008. :1-16 | Data date range
82 | Esmaili, H.,Mohd Yusof, R.,Abu Saad, H.,Ghaemian, A.,Darani Zad, N.. Association of dietary patterns with sociodemographic and health-related factors among coronary artery disease (CAD) patients. Ecol Food Nutr. 2015. 54:4-19 | Country
83 | Estradé, M.,Trude, A. C. B.,Pardilla, M.,Jock, B. W. I.,Swartz, J.,Gittelsohn, J.. Sociodemographic and Psychosocial Factors Associated With Diet Quality in 6 Rural Native American Communities. J Nutr Educ Behav. 2021. 53:10-19 | Comparator
84 | Fabian, C.,Pagan, I.,Rios, J. L.,Betancourt, J.,Cruz, S. Y.,Gonzalez, A. M.,Palacios, C.,Gonzalez, M. J.,Rivera-Soto, W. T.. Dietary Patterns and their Association with Sociodemographic Characteristics and Perceived Academic Stress of College Students in Puerto Rico. Puerto Rico Health Sciences Journal. 2013. 32:36-43 | Outcome
85 | Fan, Linlin,Baylis, Kathy,Gundersen, Craig,Ver Ploeg, Michele. Does a Nutritious Diet Cost More in Food Deserts?. 2016. :46 | Outcome
86 | Fanelli Kuczmarski, M.,Beydoun, M. A.,Cotugna, N.,Schwenk, E.,Evans, M. K.,Zonderman, A. B.. The Relationship of Diet Quality with Proportion of Daily Energy Contributed by Sandwiches Varies by Age over Adulthood in Racially and Socioeconomically Diverse Adults. Nutrients. 2020. 12 | Comparator
87 | Fanelli Kuczmarski, M.,Brewer, B. C.,Rawal, R.,Pohlig, R. T.,Zonderman, A. B.,Evans, M. K.. Aspects of Dietary Diversity Differ in Their Association with Atherosclerotic Cardiovascular Risk in a Racially Diverse US Adult Population. Nutrients. 2019; 11 (5) Fanelli Kuczmarski, M.,Brewer, B. C.,Rawal, R.,Pohlig, R. T.,Zonderman, A. B.,Evans, M. K.. Aspects of Dietary Diversity Differ in Their Association with Atherosclerotic Cardiovascular Risk in a Racially Diverse US Adult Population. Nutrients. 2019; 11 (5). | Outcome
88 | Fanelli Kuczmarski, M.,Hossain, S.,Beydoun, M. A.,Maldonando, A.,Evans, M. K.,Zonderman, A. B.. Association of DASH and Depressive Symptoms with BMI over Adulthood in Racially and Socioeconomically Diverse Adults Examined in the HANDLS Study. Nutrients. 2019. 11 | Intervention/Exposure
89 | Fanelli Kuczmarski, M.,Stave Shupe, E.,Pohlig, R. T.,Rawal, R.,Zonderman, A. B.,Evans, M. K.. A Longitudinal Assessment of Diet Quality and Risks Associated with Malnutrition in Socioeconomic and Racially Diverse Adults. Nutrients. 2019. 11: | Outcome
90 | Fang Zhang, F.,Liu, J.,Rehm, C. D.,Wilde, P.,Mande, J. R.,Mozaffarian, D.. Trends and Disparities in Diet Quality Among US Adults by Supplemental Nutrition Assistance Program Participation Status. JAMA Netw Open. 2018. 1:e180237 | Outcome
91 | Farmer, N.,Wallen, G. R.,Yang, L.,Middleton, K. R.,Kazmi, N.,Powell-Wiley, T. M.. Household Cooking Frequency of Dinner Among Non-Hispanic Black Adults is Associated with Income and Employment, Perceived Diet Quality and Varied Objective Diet Quality, HEI (Healthy Eating Index): NHANES Analysis 2007-2010. Nutrients. 2019. 11: | Comparator
92 | Ferranti, E. P.,Dunbar, S. B.,Higgins, M.,Dai, J.,Ziegler, T. R.,Frediani, J. K.,Reilly, C.,Brigham, K. L.. Psychosocial factors associated with diet quality in a working adult population. Res Nurs Health. 2013; 36 (3):242-56. #doi#. | Intervention/Exposure
93 | Ferranti, E. P.,Narayan, K. M.,Reilly, C. M.,Foster, J.,McCullough, M.,Ziegler, T. R.,Guo, Y.,Dunbar, S. B.. Dietary self-efficacy predicts AHEI diet quality in women with previous gestational diabetes. Diabetes Educ. 2014. 40:688-99 | Intervention/Exposure
94 | Fitzgerald, N.,Damio, G.,Segura-Perez, S.,Perez-Escamilla, R.. Nutrition knowledge, food label use, and food intake patterns among Latinas with and without type 2 diabetes. Journal of the American Dietetic Association. 2008. 108:960-967 | Outcome
95 | Ford, D. W.,Hartman, T. J.,Still, C.,Wood, C.,Mitchell, D. C.,Bailey, R.,Smiciklas-Wright, H.,Coffman, D. L.,Jensen, G. L.. Diet quality and body mass index are associated with health care resource use in rural older adults. J Acad Nutr Diet. 2014. 114:1932-8 | Intervention/Exposure
96 | Forrestal, S.,Potamites, E.,Guthrie, J.,Paxton, N.. Associations among Food Security, School Meal Participation, and Students’ Diet Quality in the First School Nutrition and Meal Cost Study. Nutrients. 2021. 13: | Intervention/Exposure
97 | Fowles, E. R.,Stang, J.,Bryant, M.,Kim, S.. Stress, depression, social support, and eating habits reduce diet quality in the first trimester in low-income women: a pilot study. J Acad Nutr Diet. 2012. 112:1619-25 | Intervention/Exposure
98 | Franckle, R. L.,Moran, A.,Hou, T.,Blue, D.,Greene, J.,Thorndike, A. N.,Polacsek, M.,Rimm, E. B.. Transactions at a Northeastern Supermarket Chain: Differences by Supplemental Nutrition Assistance Program Use. American Journal of Preventive Medicine. 2017. 53:E131-E138 | Outcome
99 | Franckle, R. L.,Thorndike, A. N.,Moran, A. J.,Hou, T.,Blue, D.,Greene, J. C.,Bleich, S. N.,Block, J. P.,Polacsek, M.,Rimm, E. B.. Supermarket Purchases Over the Supplemental Nutrition Assistance Program Benefit Month: A Comparison Between Participants and Nonparticipants. Am J Prev Med. 2019. 57:800-807 | Outcome
100 | Franco, M.,Diez-Roux, A. V.,Nettleton, J. A.,Lazo, M.,Brancati, F.,Caballero, B.,Glass, T.,Moore, L. V.. Availability of healthy foods and dietary patterns: the Multi-Ethnic Study of Atherosclerosis. Am J Clin Nutr. 2009. 89:897-904 | Data date range
101 | Fransen, H. P.,Boer, J. M. A.,Beulens, J. W. J.,de Wit, G. A.,Bueno-de-Mesquita, H. B.,Hoekstra, J.,May, A. M.,Peeters, P. H. M.. Associations between lifestyle factors and an unhealthy diet. Eur J Public Health. 2017. 27:274-278 | Country; Data date range
102 | Freedman, D. A.,Bell, B. A.,Clark, J.,Ngendahimana, D.,Borawski, E.,Trapl, E.,Pike, S.,Sehgal, A. R.. Small Improvements in an Urban Food Environment Resulted in No Changes in Diet Among Residents. J Community Health. 2021. 46:1-12 | Intervention/Exposure
103 | French, S. A.,Rydell, S. A.,Mitchell, N. R.,Oakes, J. M.,Elbel, B.,Harnack, L.. Financial incentives and purchase restrictions in a food benefit program affect the types of foods and beverages purchased: results from a randomized trial. International Journal of Behavioral Nutrition and Physical Activity. 2017. 14:10 | Outcome
104 | French, S. A.,Tangney, C. C.,Crane, M. M.,Wang, Y.,Appelhans, B. M.. Nutrition quality of food purchases varies by household income: the SHoPPER study. BMC Public Health. 2019. 19:231 | Outcome (Purchase data)
105 | Frongillo, E. A.,Wolfe, W. S.. Impact of participation in Home-Delivered Meals on nutrient intake, dietary patterns, and food insecurity of older persons in New York state. J Nutr Elder. 2010. 29:293-310 | Outcome; Data date range
106 | Garner, J. A.,Jilcott Pitts, S. B.,Hanson, K. L.,Ammerman, A. S.,Kolodinsky, J.,Sitaker, M. H.,Seguin-Fowler, R. A.. Making community-supported agriculture accessible to low-income families: findings from the Farm Fresh Foods for Healthy Kids process evaluation. Transl Behav Med. 2021. 11:754-763 | Intervention/Exposure
107 | Gavrieli, A.,Farr, O. M.,Davis, C. R.,Crowell, J. A.,Mantzoros, C. S.. Early life adversity and/or posttraumatic stress disorder severity are associated with poor diet quality, including consumption of trans fatty acids, and fewer hours of resting or sleeping in a US middle-aged population: A cross-sectional and prospective study. Metabolism. 2015. 64:1597-610 | Intervention/Exposure
108 | Gills, S. M. H.,Auld, G.,Hess, A.,Guenther, P. M.,Baker, S. S.. Positive Change in Healthy Eating Scores Among Adults With Low Income After Expanded Food and Nutrition Education Program Participation. J Nutr Educ Behav. 2021. | Comparator
109 | Golan, Elise H.,Stewart, Hayden,Kuchler, Fred,Dong, Diansheng. Can Low-Income Americans Afford a Healthy Diet?. 2008. :8 | Outcome
110 | Greatwood, H. C.,Daly-Smith, A.,McGregor, S.,McKenna, J.. Year 7 dietary intake: a comparison of two schools with middle-high socio-economic status. J Hum Nutr Diet. 2013. 26:563-9 | Country
111 | Greenfield, Russell. The DASH Diet. 2020 | Study design
112 | Gregory, Christian ,Ver Ploeg, Michele, Andrews, Margaret ,Coleman-Jensen, Alisha. Supplemental Nutrition Assistance Program (SNAP) Participation Leads to Modest Changes in Diet Quality. 2013; 36. | Outcome
113 | Guenther, P. M.,Luick, B. R.. Improved Overall Quality of Diets Reported by Expanded Food and Nutrition Education Program Participants in the Mountain Region. J Nutr Educ Behav. 2015. 47:421-6.e1 | Intervention/Exposure; Comparator
114 | Gupta, S.,Rose, C. M.,Buszkiewicz, J.,Ko, L. K.,Mou, J.,Cook, A.,Aggarwal, A.,Drewnowski, A.. Characterising percentage energy from ultra-processed foods by participant demographics, diet quality and diet cost: findings from the Seattle Obesity Study (SOS) III. Br J Nutr. 2020. :1-9 | Comparator
115 | Gupta, S.,Rose, C. M.,Buszkiewicz, J.,Otten, J.,Spiker, M. L.,Drewnowski, A.. Inedible Food Waste Linked to Diet Quality and Food Spending in the Seattle Obesity Study SOS III. Nutrients. 2021. 13: | Intervention/Exposure
116 | Guthrie, J. F.,Anater, A. S.,Hampton, J. C.,Catellier, D. J.,Eldridge, A. L.,Johnson, W. L.,Quann, E. E.. The Special Supplemental Nutrition Program for Women, Infants, and Children is Associated with Several Changes in Nutrient Intakes and Food Consumption Patterns of Participating Infants and Young Children, 2008 Compared with 2016. Journal of Nutrition. 2020. 150:2985-2993 | Outcome
117 | Guthrie, J. F.,Catellier, D. J.,Jacquier, E. F.,Eldridge, A. L.,Johnson, W. L.,Lutes, A. C.,Anater, A. S.,Quann, E. E.. WIC and non-WIC Infants and Children Differ in Usage of Some WIC-Provided Foods. J Nutr. 2018. 148:1547s-1556s | Outcome
118 | Guthrie, Joanne F.,Variyam, Jayachandran N.. Can Food Stamps Do More to Improve Food Choices? An Economic Perspective-Nutrition Information: Can It Improve the Diets of Low-Income Households?. 2007; 4. | Intervention/Exposure
119 | Harnack, L.,Oakes, J. M.,Elbel, B.,Beatty, T.,Rydell, S.,French, S.. Effects of Subsidies and Prohibitions on Nutrition in a Food Benefit Program: A Randomized Clinical Trial. JAMA Intern Med. 2016. 176:1610-1618 | Intervention/Exposure
120 | Harrington, J.,Fitzgerald, A. P.,Layte, R.,Lutomski, J.,Molcho, M.,Perry, I. J.. Sociodemographic, health and lifestyle predictors of poor diets. Public Health Nutrition. 2011. 14:2166-2175 | Country
121 | Hattori, A.,An, R.,Sturm, R.. Neighborhood food outlets, diet, and obesity among California adults, 2007 and 2009. Prev Chronic Dis. 2013. 10:E35 | Outcome
122 | Hidaka, B. H.,Kerling, E. H.,Thodosoff, J. M.,Sullivan, D. K.,Colombo, J.,Carlson, S. E.. Dietary patterns of early childhood and maternal socioeconomic status in a unique prospective sample from a randomized controlled trial of Prenatal DHA Supplementation. BMC Pediatr. 2016. 16:191 | Intervention/Exposure
123 | Hilmers, A.,Chen, T. A.,Cullen, K. W.. Household food insecurity and dietary intake among Mexican-American women participating in federal food assistance programs. Am J Health Promot. 2014. 28:e146-54 | Outcome
124 | Hilmers, A.,Chen, T. A.,Dave, J. M.,Thompson, D.,Cullen, K. W.. Supplemental Nutrition Assistance Program participation did not help low income Hispanic women in Texas meet the dietary guidelines. Prev Med. 2014. 62:44-8 | Outcome; Data date range
125 | Hiza, H. A.,Casavale, K. O.,Guenther, P. M.,Davis, C. A.. Diet quality of Americans differs by age, sex, race/ethnicity, income, and education level. J Acad Nutr Diet. 2013. 113:297-306 | Data date range
126 | Hsiao, P. Y.,Mitchell, D. C.,Coffman, D. L.,Allman, R. M.,Locher, J. L.,Sawyer, P.,Jensen, G. L.,Hartman, T. J.. Dietary patterns and diet quality among diverse older adults: the University of Alabama at Birmingham Study of Aging. J Nutr Health Aging. 2013. 17:19-25 | Data date range
127 | Hurley, K. M.,Black, M. M.. Commercial Baby Food Consumption and Dietary Variety in a Statewide Sample of Infants Receiving Benefits from the Special Supplemental Nutrition Program for Women, Infants, and Children. Journal of the American Dietetic Association. 2010. 110:1537-1541 | Outcome
128 | Iacobucci, Dawn. Part II: The Marketing Research Perspective: Chapter 2: Marketing Research: Consumer Behavior--Food Purchasing and Consumption. Foundations & Trends in Marketing. 2019. 13:89-91 | Intervention/Exposure
129 | Iacobucci, Dawn. Part II: The Marketing Research Perspective: Chapter 2: Marketing Research: Consumer Behavior--Food Purchasing and Consumption: 2.1: Grocery Shopping. Foundations & Trends in Marketing. 2019. 13:91-112 | Study design
130 | Jackson, J. A.,Smit, E.,Manore, M. M.,John, D.,Gunter, K.. The Family-Home Nutrition Environment and Dietary Intake in Rural Children. Nutrients. 2015. 7:9707-20 | Outcome
131 | Jansen, E. C.,Kasper, N.,Lumeng, J. C.,Brophy Herb, H. E.,Horodynski, M. A.,Miller, A. L.,Contreras, D.,Peterson, K. E.. Changes in household food insecurity are related to changes in BMI and diet quality among Michigan Head Start preschoolers in a sex-specific manner. Soc Sci Med. 2017. 181:168-176 | Intervention/Exposure
132 | Jansen, E. C.,Peterson, K. E.,Lumeng, J. C.,Kaciroti, N.,LeBourgeois, M. K.,Chen, K.,Miller, A. L.. Associations between Sleep and Dietary Patterns among Low-Income Children Attending Preschool. J Acad Nutr Diet. 2019. 119:1176-1187 | Intervention/Exposure
133 | Jilcott Pitts, S. B.,Keyserling, T. C.,Johnston, L. F.,Smith, T. W.,McGuirt, J. T.,Evenson, K. R.,Rafferty, A. P.,Gizlice, Z.,Garcia, B. A.,Ammerman, A. S.. Associations between neighborhood-level factors related to a healthful lifestyle and dietary intake, physical activity, and support for obesity prevention polices among rural adults. J Community Health. 2015. 40:276-84 | Intervention/Exposure
134 | Jilcott Pitts, S. B.,Wu, Q.,Truesdale, K. P.,Rafferty, A. P.,Haynes-Maslow, L.,Boys, K. A.,McGuirt, J. T.,Fleischhacker, S.,Johnson, N.,Kaur, A. P.,Bell, R. A.,Ammerman, A. S.,Laska, M. N.. A four-year observational study to examine the dietary impact of the North Carolina Healthy Food Small Retailer Program, 2017-2020. Int J Behav Nutr Phys Act. 2021. 18:44 | Intervention/Exposure
135 | Joyce, J. M.,Rosenkranz, R. R.,Rosenkranz, S. K.. Evaluation of Variability in Dietary Quality of School Lunches Meeting National School Lunch Program Guidelines by Socioeconomic Status and Rurality. Int J Environ Res Public Health. 2020. 17. | Outcome
136 | Jun, S.,Catellier, D. J.,Eldridge, A. L.,Dwyer, J. T.,Eicher-Miller, H. A.,Bailey, R. L.. Usual Nutrient Intakes from the Diets of US Children by WIC Participation and Income: Findings from the Feeding Infants and Toddlers Study (FITS) 2016. J Nutr. 2018. 148:1567s-1574s | Outcome
137 | Jun, S.,Cowan, A. E.,Dodd, K. W.,Tooze, J. A.,Gahche, J. J.,Eicher-Miller, H. A.,Guenther, P. M.,Dwyer, J. T.,Potischman, N.,Bhadra, A.,Forman, M. R.,Bailey, R. L.. Association of food insecurity with dietary intakes and nutritional biomarkers among US children, National Health and Nutrition Examination Survey (NHANES) 2011-2016. Am J Clin Nutr. 2021. | Intervention/Exposure
138 | Jun, S.,Zeh, M. J.,Eicher-Miller, H. A.,Bailey, R. L.. Children’s Dietary Quality and Micronutrient Adequacy by Food Security in the Household and among Household Children. Nutrients. 2019. 11: | Intervention/Exposure
139 | Juul, F.,Simões, B. D. S.,Litvak, J.,Martinez-Steele, E.,Deierlein, A.,Vadiveloo, M.,Parekh, N.. Processing level and diet quality of the US grocery cart: is there an association?. Public Health Nutr. 2019. 22:2357-2366 | Outcome (Purchase data)
140 | Jyväkorpi, S. K.,Urtamo, A.,Strandberg, T. E.. Self-Perception of Economic Means Is Associated with Dietary Choices, Diet Quality and Physical Health in the Oldest Old Men from the Highest Socioeconomic Group. J Nutr Health Aging. 2019. 23:60-62 | Country
141 | Kamdar, N.,Hughes, S. O.,Chan, W.,Power, T. G.,Meininger, J.. Indirect Effects of Food Insecurity on Body Mass Index Through Feeding Style and Dietary Quality Among Low-Income Hispanic Preschoolers. J Nutr Educ Behav. 2019. 51:876-884 | Intervention/Exposure
142 | Kang, M.,Park, S. Y.,Shvetsov, Y. B.,Wilkens, L. R.,Marchand, L. L.,Boushey, C. J.,Paik, H. Y.. Sex differences in sociodemographic and lifestyle factors associated with diet quality in a multiethnic population. Nutrition. 2019. 66:147-152 | Intervention/Exposure
143 | Kant, A. K.,Graubard, B. I.. Secular trends in regional differences in nutritional biomarkers and self-reported dietary intakes among American adults: National Health and Nutrition Examination Survey (NHANES) 1988-1994 to 2009-2010. Public Health Nutr. 2018. 21:927-939 | Intervention/Exposure
144 | Karimbeiki, R.,Pourmasoumi, M.,Feizi, A.,Abbasi, B.,Hadi, A.,Rafie, N.,Safavi, S. M.. Higher dietary diversity score is associated with obesity: a case-control study. Public Health. 2018. 157:127-134 | Country
145 | Karpyn, A.,Young, C. R.,Collier, Z.,Glanz, K.. Correlates of Healthy Eating in Urban Food Desert Communities. Int J Environ Res Public Health. 2020. 17 | Intervention/Exposure
146 | Kay, M. C.,Wasser, H.,Adair, L. S.,Thompson, A. L.,Siega-Riz, A. M.,Suchindran, C. M.,Bentley, M. E.. Consumption of key food groups during the postpartum period in low-income, non-Hispanic black mothers. Appetite. 2017. 117:161-167 | Outcome
147 | Kegler, M. C.,Prakash, R.,Hermstad, A.,Anderson, K.,Haardörfer, R.,Raskind, I. G.. Food Acquisition Practices, Body Mass Index, and Dietary Outcomes by Level of Rurality. J Rural Health. 2020. | Outcome
148 | Keita, A. D.,Casazza, K.,Thomas, O.,Fernandez, J. R.. Neighborhood-level disadvantage is associated with reduced dietary quality in children. J Am Diet Assoc. 2009. 109:1612-6 | Outcome
149 | Kell, K. P.,Judd, S. E.,Pearson, K. E.,Shikany, J. M.,Fernández, J. R.. Associations between socio-economic status and dietary patterns in US black and white adults. Br J Nutr. 2015. 113:1792-9 | Data date range
150 | Kharmats, A. Y.,Jones-Smith, J. C.,Cheah, Y. S.,Budd, N.,Flamm, L.,Cuccia, A.,Mui, Y.,Trude, A.,Gittelsohn, J.. Relation between the Supplemental Nutritional Assistance Program cycle and dietary quality in low-income African Americans in Baltimore, Maryland. Am J Clin Nutr. 2014. 99:1006-14 | Outcome
151 | Kilanowski, J. F.,Moore, L. C.. Food security and dietary intake in midwest migrant farmworker children. J Pediatr Nurs. 2010. 25:360-6 | Data date range
152 | Kilanowski, J. F.. Patterns and correlates of nutrition among migrant farm-worker children. West J Nurs Res. 2012. 34:396-416 | Intervention/Exposure
153 | Kolodinsky, Jane M.,Sitaker, Marilyn,Morgan, Emily H.,Connor, Leah M.,Hanson, Karla L.,Becot, Florence,Pitts, Stephanie B. Jilcott,Ammerman, Alice S.,Seguin, Rebecca A.. Can CSA Cost-Offset Programs Improve Diet Quality for Limited Resource Families?. 2017. 32:10 | Study design
154 | Kranz, S.,McCabe, G. P.. Examination of the five comparable component scores of the diet quality indexes HEI-2005 and RC-DQI using a nationally representative sample of 2-18 year old children: NHANES 2003-2006. J Obes. 2013. 2013:376314 | Data date range
155 | Lacko, A.,Delamater, P.,Gordon-Larsen, P.,Wen Ng, S.. Geographic patterns and socioeconomic differences in the nutritional quality of household packaged food purchases in the United States. Health Place. 2021. 69:102567 | Outcome (Purchase data)
156 | Lacko, A.,Ng, S. W.,Popkin, B.. Urban vs.. Rural Socioeconomic Differences in the Nutritional Quality of Household Packaged Food Purchases by Store Type. Int J Environ Res Public Health. 2020. 17 | Outcome
157 | Larson, N.,Laska, M. N.,Neumark-Sztainer, D.. Food Insecurity, Diet Quality, Home Food Availability, and Health Risk Behaviors Among Emerging Adults: Findings From the EAT 2010-2018 Study. Am J Public Health. 2020. 110:1422-1428 | Outcome; Comparator
158 | LeCroy, M. N.,Nicastro, H. L.,Truesdale, K. P.,Matheson, D. M.,Ievers-Landis, C. E.,Pratt, C. A.,Jones, S.,Sherwood, N. E.,Burgess, L. E.,Robinson, T. N.,Yang, S.,Stevens, J.. Dietary patterns and associations with BMI in low-income, ethnic minority youth in the USA according to baseline data from four randomised controlled trials. Br J Nutr. 2020. :1-11 | Comparator
159 | LeDoux, T. F.,Vojnovic, I.. Examining the role between the residential neighborhood food environment and diet among low-income households in Detroit, Michigan. Applied Geography. 2014. 55:9-18 | Outcome
160 | Lee, J.,Kubik, M. Y.,Fulkerson, J. A.. Diet Quality and Fruit, Vegetable, and Sugar-Sweetened Beverage Consumption by Household Food Insecurity among 8- to 12-Year-Old Children during Summer Months. J Acad Nutr Diet. 2019. 119:1695-1702 | Intervention/Exposure
161 | Lee, Jonq-Ying. Food Assistance Programs and Healthy Diet among Low-Income Individuals. 2009. :5 | Data date range
162 | Lee, R.,Zhai, F.,Han, W. J.,Brooks-Gunn, J.,Waldfogel, J.. “Head Start and Children’s Nutrition, Weight, and Health Care Receipt”. Early Child Res Q. 2013. 28 | Data date range
163 | Leung, C. W.,Cluggish, S.,Villamor, E.,Catalano, P. J.,Willett, W. C.,Rimm, E. B.. Few changes in food security and dietary intake from short-term participation in the Supplemental Nutrition Assistance Program among low-income Massachusetts adults. J Nutr Educ Behav. 2014. 46:68-74 | Outcome
164 | Leung, C. W.,Epel, E. S.,Ritchie, L. D.,Crawford, P. B.,Laraia, B. A.. Food insecurity is inversely associated with diet quality of lower-income adults. J Acad Nutr Diet. 2014. 114:1943-53.e2 | Intervention/Exposure
165 | Leung, C. W.,Tester, J. M.. The Association between Food Insecurity and Diet Quality Varies by Race/Ethnicity: An Analysis of National Health and Nutrition Examination Survey 2011-2014 Results. J Acad Nutr Diet. 2019. 119:1676-1686 | Intervention/Exposure
166 | Leung, C. W.,Wolfson, J. A.,Lahne, J.,Barry, M. R.,Kasper, N.,Cohen, A. J.. Associations between Food Security Status and Diet-Related Outcomes among Students at a Large, Public Midwestern University. J Acad Nutr Diet. 2019. 119:1623-1631 | Outcome
167 | Leung, C. W.,Wolfson, J. A.. Food Insecurity Among Older Adults: 10-Year National Trends and Associations with Diet Quality. J Am Geriatr Soc. 2021. 69:964-971 | Intervention/Exposure
168 | Lin, Biing-Hwan. Diet Quality Usually Varies by Income Status. 2005. :2
169 | Lin, D.,Zickgraf, H.,Butt, M.,Rigby, A.. Food insecurity is linked to poorer dietary quality in prebariatric surgery patients. Surg Obes Relat Dis. 2021. 17:263-270 | Outcome
170 | Link, L. B.,Jacobson, J. S.. Factors affecting adherence to a raw vegan diet. Complement Ther Clin Pract. 2008. 14:53-9 | Data date range
171 | Lipsky, L. M.,Nansel, T. R.,Haynie, D. L.,Liu, D.,Li, K.,Pratt, C. A.,Iannotti, R. J.,Dempster, K. W.,Simons-Morton, B.. Diet quality of US adolescents during the transition to adulthood: changes and predictors. Am J Clin Nutr. 2017. 105:1424-1432 | Intervention/Exposure
172 | Litvak, J.,Parekh, N.,Juul, F.,Deierlein, A.. Food assistance programs and income are associated with the diet quality of grocery purchases for households consisting of women of reproductive age or young children. Prev Med. 2020. 138:106149 | Outcome (Purchase data)
173 | Liu, J.,Micha, R.,Li, Y.,Mozaffarian, D.. Trends in Food Sources and Diet Quality Among US Children and Adults, 2003-2018. JAMA Netw Open. 2021. 4:e215262 | Outcome
174 | Liu, Y.,Zhang, Y.,Remley, D. T.,Eicher-Miller, H. A.. Frequency of Food Pantry Use Is Associated with Diet Quality among Indiana Food Pantry Clients. J Acad Nutr Diet. 2019. 119:1703-1712 | Intervention/Exposure
175 | Lyerly, R.,Rummo, P.,Amin, S.,Evans, W.,Cohen, E. D.,Lawson, E.,Hallett, E.,De-Oliveira, S.,Rose, J.,Sutten Coats, C.,Nunn, A.. Effectiveness of mobile produce markets in increasing access and affordability of fruits and vegetables among low-income seniors. Public Health Nutr. 2020. 23:3226-3235 | Outcome
176 | Ma, C.,Ho, S. K. M.,Singh, S.,Choi, M. Y.. Gender Disparities in Food Security, Dietary Intake, and Nutritional Health in the United States. Am J Gastroenterol. 2021. 116:584-592 | Outcome
177 | Madrigal, J. M.,Cedillo-Couvert, E.,Ricardo, A. C.,Appel, L. J.,Anderson, C. A. M.,Deo, R.,Hamm, L. L.,Cornish-Zirker, D.,Tan, T. C.,Sha, D.,Hsu, J. Y.,Zenk, S. N.,Saunders, M. R.,Persky, V.,Lash, J. P.. Neighborhood Food Outlet Access and Dietary Intake among Adults with Chronic Kidney Disease: Results from the Chronic Renal Insufficiency Cohort Study. J Acad Nutr Diet. 2020. 120:1151-1162.e3 | Intervention/Exposure
178 | Mancino, Lisa ,Gregory, Christian A.. Food-Insecure Households Score Lower on Diet Quality Compared to Food-Secure Households. 2020; March 2020 (02) | Outcome
179 | Mancino, Lisa, Guthrie, Joanne. SNAP Households Must Balance Multiple Priorities To Achieve a Healthful Diet. 2014; (10):1. | Outcome
180 | Marmash, D.,Ha, K.,Sakaki, J. R.,Gorski, I.,Rule, B.,Foster, J.,Puglisi, M.,Chun, O. K.. Diet Quality, Nutritional Adequacy, and Sociodemographic Characteristics of Mobile Food Pantry Users in Northeastern Connecticut. Nutrients. 2021. 13 | Outcome
181 | Mayne, S. L.,Virudachalam, S.,Fiks, A. G.. Clustering of unhealthy behaviors in a nationally representative sample of U.S. children and adolescents. Prev Med. 2020. 130:105892 | Intervention/Exposure; Outcome; Comparator
182 | McClain, A. C.,Tucker, K. L.,Falcon, L. M.,Mattei, J.. Food insecurity and dietary intake by Supplemental Nutrition Assistance Program participation status among mainland US Puerto Rican adults after the 2009 American Recovery and Reinvestment Act. Public Health Nutrition. 2019. 22:2989-2998 | Outcome
183 | Merhout, F.,Doyle, J.. Socioeconomic Status and Diet Quality in College Students. J Nutr Educ Behav. 2019. 51:1107-1112 | Outcome
184 | Metzgar, M.,Rideout, T. C.,Fontes-Villalba, M.,Kuipers, R. S.. The feasibility of a Paleolithic diet for low-income consumers. Nutr Res. 2011. 31:444-51 | Comparator; Data date range
185 | Millstein, R. A.,Yeh, H. C.,Brancati, F. L.,Batts-Turner, M.,Gary, T. L.. Food availability, neighborhood socioeconomic status, and dietary patterns among blacks with type 2 diabetes mellitus. Medscape J Med. 2009. 11:15 | Data date range
186 | Misyak, S. A.,Hedrick, V. E.,Pudney, E.,Serrano, E. L.,Farris, A. R.. Reliability of a Market Basket Assessment Tool (MBAT) for Use in SNAP-Ed Healthy Retail Initiatives. J Nutr Educ Behav. 2018. 50:511-515 | Intervention/Exposure
187 | Molitor, F.,Doerr, C.,Pugliese, J.,Whetstone, L.. Three-year trends in dietary behaviours among mothers, teenagers and children from SNAP-Ed (Supplemental Nutrition Assistance Program-Education) eligible households across California. Public Health Nutr. 2020. 23:3-12 | Intervention/Exposure
188 | Molitor, F.,Sugerman, S. B.,Sciortino, S.. Fruit and Vegetable, Fat, and Sugar-Sweetened Beverage Intake Among Low-Income Mothers Living in Neighborhoods With Supplemental Nutrition Assistance Program-Education. J Nutr Educ Behav. 2016. 48:683-690.e1 | Intervention/Exposure
189 | Monsivais, P.,Drewnowski, A.. Lower-energy-density diets are associated with higher monetary costs per kilocalorie and are consumed by women of higher socioeconomic status. J Am Diet Assoc. 2009. 109:814-22 | Data date range
190 | Monsivais, P.,Rehm, C. D.,Drewnowski, A.. The DASH diet and diet costs among ethnic and racial groups in the United States. JAMA Intern Med. 2013. 173:1922-4 | Data date range
191 | Moore, L. V.,Diez Roux, A. V.,Nettleton, J. A.,Jacobs, D. R., Jr.. Associations of the local food environment with diet quality--a comparison of assessments based on surveys and geographic information systems: the multi-ethnic study of atherosclerosis. Am J Epidemiol. 2008. 167:917-24 | Data date range
192 | Mousa, T. Y.,Freeland-Graves, J. H.. Food security of food recipients of a food pantry and soup kitchen. Public Health Nutr. 2019. 22:1451-1460 | Intervention/Exposure
193 | Muhammad, J. N.,Fernandez, J. R.,Clay, O. J.,Saag, M. S.,Overton, E. T.,Willig, A. L.. Associations of food insecurity and psychosocial measures with diet quality in adults aging with HIV. AIDS Care. 2019. 31:554-562 | Intervention/Exposure
194 | Mulik, K.,Haynes-Maslow, L.. The Affordability of MyPlate: An Analysis of SNAP Benefits and the Actual Cost of Eating According to the Dietary Guidelines. J Nutr Educ Behav. 2017. 49:623-631.e1 | Intervention/Exposure
195 | Mullany, B.,Neault, N.,Tsingine, D.,Powers, J.,Lovato, V.,Clitso, L.,Massey, S.,Talgo, A.,Speakman, K.,Barlow, A.. Food insecurity and household eating patterns among vulnerable American-Indian families: associations with caregiver and food consumption characteristics. Public Health Nutr. 2013. 16:752-60 | Outcome
196 | Mullie, P.,Clarys, P.,Hulens, M.,Vansant, G.. Dietary patterns and socioeconomic position. Eur J Clin Nutr. 2010. 64:231-8 | Country; Data date range
197 | Newby, P. K.,Noel, S. E.,Grant, R.,Judd, S.,Shikany, J. M.,Ard, J.. Race and region have independent and synergistic effects on dietary intakes in black and white women. Nutr J. 2012. 11:25 | Outcome
198 | Ng, S. W.,Poti, J. M.,Popkin, B. M.. Trends in racial/ethnic and income disparities in foods and beverages consumed and purchased from stores among US households with children, 2000-2013. Am J Clin Nutr. 2016. 104:750-9 | Outcome
199 | Nguyen, B. T.,Han, X.,Jemal, A.,Drope, J.. Diet quality, risk factors and access to care among low-income uninsured American adults in states expanding Medicaid vs.. states not expanding under the affordable care act. Prev Med. 2016. 91:169-171 | Intervention/Exposure
200 | Nnakwe, Nweze E.. Dietary Patterns and Prevalence of Food Insecurity Among Low-Income Families Participating in Community Food Assistance Programs in a Midwest Town. Family & Consumer Sciences Research Journal. 2008. 36:229-242 | Data date range
201 | Of Health, Mississippi State Department. Nutrition, Weight Loss and Healthy Eating - Mississippi State Department of Health. 2021. | Study design
202 | Ozcan, B. A.,Yesilkay, B.,Yaldiz, N.,Pehliva, M.. Factors affecting diet quality in adolescents: the effect of sociodemographic characteristics and meal consumption. Progress in Nutrition. 2020. 22:8 | Country
203 | Palmer, S. M.,Knoblauch, S. T.,Winham, D. M.,Hiller, M. B.,Shelley, M. C.. Putting Knowledge into Practice: Low-Income Women Talk about Food Choice Decisions. Int J Environ Res Public Health. 2020. 17 | Outcome
204 | Park, S. Y.,Shvetsov, Y. B.,Kang, M.,Setiawan, V. W.,Wilkens, L. R.,Le Marchand, L.,Boushey, C. J.. Changes in Diet Quality over 10 Years Are Associated with Baseline Sociodemographic and Lifestyle Factors in the Multiethnic Cohort Study. J Nutr. 2020. 150:1880-1888 | Intervention/Exposure
205 | Park, Y.,Neckerman, K.,Quinn, J.,Weiss, C.,Jacobson, J.,Rundle, A.. Neighbourhood immigrant acculturation and diet among Hispanic female residents of New York City. Public Health Nutr. 2011. 14:1593-600 | Data date range
206 | Parker, H. W.,Tovar, A.,McCurdy, K.,Vadiveloo, M.. Socio-economic and racial prenatal diet quality disparities in a national US sample. Public Health Nutr. 2020. 23:894-903 | Data date range
207 | Perkins, S.,Daley, A.,Yerxa, K.,Therrien, M.. The Effectiveness of the Expanded Food and Nutrition Education Program (EFNEP) on Diet Quality as Measured by the Healthy Eating Index. Am J Lifestyle Med. 2020. 14:316-325 | Comparator
208 | Pfledderer, C. D.,Gren, L. H.,Metos, J.,Brusseau, T. A.,O’Toole, K.,Buys, S. S.,Daly, M. B.,Frost, C. J.. Mothers’ Diet and Family Income Predict Daughters’ Healthy Eating. Prev Chronic Dis. 2021. 18:E24 | Country
209 | Pooler, J. A.,Srinivasan, M.,Wong, K.,Blitstein, J. L.. Food Skills Education and Low-Income Adults’ Healthy Food Choices. Int Q Community Health Educ. 2021. :272684x211004941 | Intervention/Exposure; Comparator
210 | Poskute, A. S.,Nzesi, A.,Geliebter, A.. Changes in food intake during the COVID-19 pandemic in New York City. Appetite. 2021. 163:105191 | Outcome
211 | Ralston, P. A.,Cohen, N. L.,Wickrama, K.,Kwag, K.. Social Support and Dietary Quality in Older African American Public Housing Residents. Research on Aging. 2011. 33:688-712 | Data date range
212 | Raskind, I. G.,Kegler, M. C.,Girard, A. W.,Dunlop, A. L.,Kramer, M. R.. An activity space approach to understanding how food access is associated with dietary intake and BMI among urban, low-income African American women. Health Place. 2020. 66:102458 | Outcome
213 | Rawal, R.,Kuczmarski, M. F.,Cotugna, N.,Brewer, B. C.,Beydoun, M. A.,Hughes, V. C.,Zonderman, A. B.,Evans, M. K.. Aspects of Dietary Diversity Changes across Adulthood in Racially Diverse Adults. Nutrients. 2020; 12 (8) | Outcome
214 | Rehm, C. D.,Monsivais, P.,Drewnowski, A.. Relation between diet cost and Healthy Eating Index 2010 scores among adults in the United States 2007-2010. Prev Med. 2015. 73:70-5 | Intervention/Exposure
215 | Rex, S. M.,Kopetsky, A.,Bodt, B.,Robson, S. M.. Relationships Among the Physical and Social Home Food Environments, Dietary Intake, and Diet Quality in Mothers and Children. J Acad Nutr Diet. 2021. | Intervention/Exposure
216 | Richardson, A. S.,Collins, R. L.,Ghosh-Dastidar, B.,Ye, F.,Hunter, G. P.,Baird, M. D.,Schwartz, H.,Sloan, J. C.,Nugroho, A.,Beckman, R.,Troxel, W. M.,Gary-Webb, T. L.,Dubowitz, T.. Improvements in Neighborhood Socioeconomic Conditions May Improve Resident Diet. Am J Epidemiol. 2021. 190:798-806 | Comparator
217 | Rifas-Shiman, S. L.,Rich-Edwards, J. W.,Kleinman, K. P.,Oken, E.,Gillman, M. W.. Dietary quality during pregnancy varies by maternal characteristics in Project Viva: a US cohort. J Am Diet Assoc. 2009. 109:1004-11 | Data date range
218 | Rivera, R. L.,Zhang, Y.,Wang, Q.,Maulding, M. K.,Tooze, J. A.,Wright, B. N.,Craig, B. A.,Bailey, R. L.,Eicher-Miller, H. A.. Diet Quality and Associations with Food Security among Women Eligible for Indiana Supplemental Nutrition Assistance Program-Education. J Nutr. 2020. 150:2191-2198 | Intervention/Exposure
219 | Rose, C. M.,Gupta, S.,Buszkiewicz, J.,Ko, L. K.,Mou, J.,Cook, A.,Moudon, A. V.,Aggarwal, A.,Drewnowski, A.. Small increments in diet cost can improve compliance with the Dietary Guidelines for Americans. Soc Sci Med. 2020. 266:113359 | Intervention/Exposure
220 | Rose, D.,Heller, M. C.,Willits-Smith, A. M.,Meyer, R. J.. Carbon footprint of self-selected US diets: nutritional, demographic, and behavioral correlates. Am J Clin Nutr. 2019. 109:526-534 | Intervention/Exposure; Outcome
221 | Rossen, L. M.,Kobernik, E. K.. Food insecurity and dietary intake among US youth, 2007-2010. Pediatr Obes. 2016. 11:187-93 | Outcome
222 | Rummo, P. E.,Meyer, K. A.,Boone-Heinonen, J.,Jacobs, D. R., Jr.,Kiefe, C. I.,Lewis, C. E.,Steffen, L. M.,Gordon-Larsen, P.. Neighborhood availability of convenience stores and diet quality: findings from 20 years of follow-up in the coronary artery risk development in young adults study. Am J Public Health. 2015. 105:e65-73 | Data date range
223 | Sanjeevi, N.,Freeland-Graves, J. H.. Association of Grocery Expenditure Relative to Thrifty Food Plan Cost with Diet Quality of Women Participating in the Supplemental Nutrition Assistance Program. J Acad Nutr Diet. 2018. 118:2315-2323 | Comparator
224 | Sanjeevi, N.,Freeland-Graves, J.,Hersh, M.. Food insecurity, diet quality and body mass index of women participating in the Supplemental Nutrition Assistance Program: The role of intrapersonal, home environment, community and social factors. Appetite. 2018. 125:109-117 | Intervention/Exposure
225 | Sanjeevi, N.,Freeland-Graves, J.. Monthly Variations in Dietary Intake of Women Participating in the Supplemental Nutrition Assistance Program. J Acad Nutr Diet. 2019. 119:261-271 | Intervention/Exposure
226 | Saxe-Custack, A.,LaChance, J.,Hanna-Attisha, M.,Ceja, T.. Fruit and Vegetable Prescriptions for Pediatric Patients Living in Flint, Michigan: A Cross-Sectional Study of Food Security and Dietary Patterns at Baseline. Nutrients. 2019. 11 | Intervention/Exposure; Outcome
227 | Shah, B. S.,Freeland-Graves, J. H.,Cahill, J. M.,Lu, H.,Graves, G. R.. Diet quality as measured by the healthy eating index and the association with lipid profile in low-income women in early postpartum. J Am Diet Assoc. 2010. 110:274-9 | Data date range
228 | Sharkey, J. R.,Nalty, C.,Johnson, C. M.,Dean, W. R.. Children’s very low food security is associated with increased dietary intakes in energy, fat, and added sugar among Mexican-origin children (6-11 y) in Texas border Colonias. BMC Pediatr. 2012. 12:16 | Outcome
229 | Sharpe, P. A.,Whitaker, K.,Alia, K. A.,Wilcox, S.,Hutto, B.. Dietary Intake, Behaviors and Psychosocial Factors Among Women from Food-Secure and Food-Insecure Households in the United States. Ethn Dis. 2016. 26:139-46 | Intervention/Exposure
230 | Shiao, S. P. K.,Grayson, J.,Lie, A.,Yu, C. H.. Predictors of the Healthy Eating Index and Glycemic Index in Multi-Ethnic Colorectal Cancer Families. Nutrients. 2018. 10 | Intervention/Exposure
231 | Shin, Dayeon,Lee, Kyung Won,Song, Won O.. Pre-Pregnancy Weight Status Is Associated with Diet Quality and Nutritional Biomarkers during Pregnancy. Nutrients. 2016; 8 (3):162. | Outcome
232 | Silveira, B. K. S.,de Novaes, J. F.,Vieira, S. A.,Rocha, Dmup,Leal, A. C. G.,Hermsdorff, H. H. M.. Sociodemographic characteristics and dietary patterns in cardiometabolic risk subjects. British Food Journal. 2019. 121:2780-2790 | Country
233 | Spees, C. K.,Clark, J. E.,Hooker, N. H.,Watowicz, R. P.,Taylor, C. A.. Dietary Intake Contributions of Food and Beverages by Source and Food Security Status in US Adults. J Nutr Educ Behav. 2017. 49:667-673.e1 | Intervention/Exposure
234 | Stein, C.,Cunha-Cruz, J.,Hugo, F. N.. Is dietary pattern a mediator of the relationship between socioeconomic status and dental caries?. Clin Oral Investig. 2021. : | Intervention/Exposure
235 | Stephenson, B. J. K.,Sotres-Alvarez, D.,Siega-Riz, A. M.,Mossavar-Rahmani, Y.,Daviglus, M. L.,Van Horn, L.,Herring, A. H.,Cai, J.. Empirically Derived Dietary Patterns Using Robust Profile Clustering in the Hispanic Community Health Study/Study of Latinos. J Nutr. 2020. 150:2825-2834 | Intervention/Exposure
236 | Surkan, P. J.,Coutinho, A. J.,Christiansen, K.,Dennisuk, L. A.,Suratkar, S.,Mead, E.,Sharma, S.,Gittelsohn, J.. Healthy food purchasing among African American youth: associations with child gender, adult caregiver characteristics and the home food environment. Public Health Nutrition. 2011. 14:670-677 | Outcome
237 | Taillie, L. S.,Ng, S. W.,Xue, Y.,Harding, M.. Deal or no deal? The prevalence and nutritional quality of price promotions among U.S. food and beverage purchases. Appetite. 2017. 117:365-372 | Outcome
238 | Tan, M. L.,Laraia, B.,Madsen, K. A.,Au, L. E.,Frongillo, E. A.,Ritchie, L. D.. Child Food Insecurity Is Associated with Energy Intake among Fourth- and Fifth-Grade Girls. J Acad Nutr Diet. 2019. 119:1722-1731.e2 | Intervention/Exposure
239 | Taylor, Christopher A.,Spees, Colleen K.,Markwordt, Alayna M.,Watowicz, Rosanna P.,Clark, Jill K.,Hooker, Neal H.. Differences in US Adult Dietary Patterns by Food Security Status. Journal of Consumer Affairs. 2017. 51:549-565 | Intervention/Exposure
240 | Teufel-Shone, N. I.,Jiang, L. H.,Beals, J.,Henderson, W. G.,Zhang, L. J.,Acton, K. J.,Roubideaux, Y.,Manson, S. M.. Demographic characteristics and food choices of participants in the Special Diabetes Program for American Indians Diabetes Prevention Demonstration Project. Ethnicity & Health. 2015. 20:327-340 | Data date range
241 | Thompson, T. L.,Singleton, C. R.,Springfield, S. E.,Thorpe, R. J., Jr.,Odoms-Young, A.. Differences in Nutrient Intake and Diet Quality Between Non-Hispanic Black and Non-Hispanic White Men in the United States. Public Health Rep. 2020. 135:334-342 | Comparator
242 | Thomson, J. L.,Onufrak, S. J.,Connell, C. L.,Zoellner, J. M.,Tussing-Humphreys, L. M.,Bogle, M. L.,Yadrick, K.. Food and beverage choices contributing to dietary guidelines adherence in the Lower Mississippi Delta. Public Health Nutr. 2011. 14:2099-109 | Data date range
243 | Thomson, J. L.,Zoellner, J. M.,Tussing-Humphreys, L. M.,Goodman, M. H.. Moderators of intervention dose effects on diet quality and physical activity changes in a church-based, multicomponent, lifestyle study: Delta Body and Soul III. Health Educ Res. 2016. 31:339-49 | Intervention/Exposure
244 | Todd, Jessica E.. Changes in Eating Patterns and Diet Quality Among Working-Age Adults, 2005-2010. 2014 | Outcome
245 | Torres-Aguilar, P.,Teran-Garcia, M.,Wiley, A.,Raffaelli, M.,Morales, M.. Factors Correlated to Protective and Risk Dietary Patterns in Immigrant Latino Mothers in Non-metropolitan Rural Communities. J Immigr Minor Health. 2016. 18:652-659 | Outcome
246 | Townsend, M. S.,Aaron, G. J.,Monsivais, P.,Keim, N. L.,Drewnowski, A.. Less-energy-dense diets of low-income women in California are associated with higher energy-adjusted diet costs. Am J Clin Nutr. 2009. 89:1220-6 | Data date range
247 | Tran, L. T.,Brewster, P. J.,Chidambaram, V.,Hurdle, J. F.. Towards Measuring the Food Quality of Grocery Purchases: an Estimation Model of the Healthy Eating Index-2010 Using only Food Item Counts. Procedia Food Sci. 2015. 4:148-159 | Intervention/Exposure
248 | Trapp, C. M.,Burke, G.,Gorin, A. A.,Wiley, J. F.,Hernandez, D.,Crowell, R. E.,Grant, A.,Beaulieu, A.,Cloutier, M. M.. The relationship between dietary patterns, body mass index percentile, and household food security in young urban children. Child Obes. 2015. 11:148-55 | Outcome
249 | Treviño, R. P.,Vasquez, L.,Shaw-Ridley, M.,Mosley, D.,Jechow, K.,Piña, C.. Outcome of a food observational study among low-income preschool children participating in a family-style meal setting. Health Educ Behav. 2015. 42:240-8 | Intervention/Exposure; Outcome; Comparator
250 | Trude, A. C. B.,Black, M. M.,Surkan, P. J.,Hurley, K. M.,Wang, Y.. Maternal anxiety and diet quality among mothers and toddlers from low-income households. Matern Child Nutr. 2020. 16:e12992 | Comparator
251 | Truesdale, K. P.,Matheson, D. M.,JaKa, M. M.,McAleer, S.,Sommer, E. C.,Pratt, C. A.. Baseline diet quality of predominantly minority children and adolescents from households characterized by low socioeconomic status in the Childhood Obesity Prevention and Treatment Research (COPTR) Consortium. BMC Nutr. 2019. 5:38 | Intervention/Exposure
252 | Vadiveloo, M. K.,Parker, H. W.,Juul, F.,Parekh, N.. Sociodemographic Differences in the Dietary Quality of Food-at-Home Acquisitions and Purchases among Participants in the U.S. Nationally Representative Food Acquisition and Purchase Survey (FoodAPS). Nutrients. 2020. 12: | Outcome (Purchase data)
253 | Vadiveloo, M.,Guan, X.,Parker, H. W.,Perraud, E.,Buchanan, A.,Atlas, S.,Thorndike, A. N.. Effect of Personalized Incentives on Dietary Quality of Groceries Purchased: A Randomized Crossover Trial. JAMA Netw Open. 2021. 4:e2030921 | Intervention/Exposure
254 | Vadiveloo, M.,Perraud, E.,Parker, H. W.,Juul, F.,Parekh, N.. Geographic Differences in the Dietary Quality of Food Purchases among Participants in the Nationally Representative Food Acquisition and Purchase Survey (FoodAPS). Nutrients. 2019. 11: | Outcome (Purchase data)
255 | Ver Ploeg, Michele,Rahko vs.ky, Ilya. Recent Evidence on the Effects of Food Store Access on Food Choice and Diet Quality. 2016. :1 | Outcome; Study design
256 | Wang, D. D.,Leung, C. W.,Li, Y.,Ding, E. L.,Chiuve, S. E.,Hu, F. B.,Willett, W. C.. Trends in dietary quality among adults in the United States, 1999 through 2010. JAMA Intern Med. 2014. 174:1587-95 | Outcome
257 | Wang, Y.,Chen, X.. How much of racial/ethnic disparities in dietary intakes, exercise, and weight status can be explained by nutrition- and health-related psychosocial factors and socioeconomic status among US adults?. J Am Diet Assoc. 2011. 111:1904-11 | Data date range
258 | Wang, Y.,Jahns, L.,Tussing-Humphreys, L.,Xie, B.,Rockett, H.,Liang, H.,Johnson, L.. Dietary intake patterns of low-income urban african-american adolescents. J Am Diet Assoc. 2010. 110:1340-5 | Intervention/Exposure
259 | Weinfield, N. S.,Borger, C.,Au, L. E.,Whaley, S. E.,Berman, D.,Ritchie, L. D.. Longer Participation in WIC Is Associated with Better Diet Quality in 24-Month-Old Children. J Acad Nutr Diet. 2020. 120:963-971 | Intervention/Exposure
260 | Wen, X.,Kong, K. L.,Eiden, R. D.,Sharma, N. N.,Xie, C.. Sociodemographic differences and infant dietary patterns. Pediatrics. 2014. 134:e1387-98 | Data date range
261 | Whiteman, E. D.,Chrisinger, B. W.,Hillier, A.. Diet Quality Over the Monthly Supplemental Nutrition Assistance Program Cycle. Am J Prev Med. 2018. 55:205-212 | Outcome (Purchase data)
262 | Wilson, Magdalena M.,Reedy, Jill,Krebs-Smith, Susan M.. American Diet Quality: Where It Is, Where It Is Heading, and What It Could Be. Journal of the Academy of Nutrition and Dietetics. 2016. 116:302-310.e1 | Intervention/Exposure
263 | Woodruff, R. C.,Haardörfer, R.,Raskind, I. G.,Hermstad, A.,Kegler, M. C.. Comparing food desert residents with non-food desert residents on grocery shopping behaviours, diet and BMI: results from a propensity score analysis. Public Health Nutr. 2020. 23:806-811 | Outcome
264 | Wright, B. N.,Bailey, R. L.,Craig, B. A.,Mattes, R. D.,McCormack, L.,Stluka, S.,Franzen-Castle, L.,Henne, B.,Mehrle, D.,Remley, D.,Eicher-Miller, H. A.. Daily Dietary Intake Patterns Improve after Visiting a Food Pantry among Food-Insecure Rural Midwestern Adults. Nutrients. 2018. 10: | Intervention/Exposure
265 | Wright, B. N.,Tooze, J. A.,Bailey, R. L.,Liu, Y.,Rivera, R. L.,McCormack, L.,Stluka, S.,Franzen-Castle, L.,Henne, B.,Mehrle, D.,Remley, D.,Eicher-Miller, H. A.. Dietary Quality and Usual Intake of Underconsumed Nutrients and Related Food Groups Differ by Food Security Status for Rural, Midwestern Food Pantry Clients. J Acad Nutr Diet. 2020. 120:1457-1468 | Intervention/Exposure
266 | Wright, B. N.,Vasquez-Mejia, C. M.,Guenther, P. M.,McCormack, L.,Stluka, S.,Franzen-Castle, L.,Henne, B.,Mehrle, D.,Remley, D.,Eicher-Miller, H. A.. Fruit and Vegetable Healthy Eating Index Component Scores of Distributed Food Bags Were Positively Associated with Client Diet Scores in a Sample of Rural, Midwestern Food Pantries. J Acad Nutr Diet. 2021. 121:74-83 | Intervention/Exposure
267 | Young, C. M.,Batch, B. C.,Svetkey, L. P.. Effect of socioeconomic status on food availability and cost of the Dietary Approaches to Stop Hypertension (DASH) dietary pattern. J Clin Hypertens (Greenwich). 2008. 10:603-11 | Data date range
268 | Zarnowiecki, D.,Ball, K.,Parletta, N.,Dollman, J.. Describing socioeconomic gradients in children’s diets - does the socioeconomic indicator used matter?. Int J Behav Nutr Phys Act. 2014. 11:44 | Country
269 | Zhang, Q.,Wang, Y. F.. Socioeconomic and Racial/Ethnic Disparity in Americans’ Adherence to Federal Dietary Recommendations. Journal of the Academy of Nutrition and Dietetics. 2012. 112:614-616 | Study design
270 | Zimmer, M. C.,Rubio, V.,Kintziger, K. W.,Barroso, C.. Racial/Ethnic Disparities in Dietary Intake of U.S. Children Participating in WIC. Nutrients. 2019. 11 | Outcome
271 | Zimmer, M. C.,Vernarelli, J. A.. Select Food Group Intake of US Children Aged 2 to 4 Years by WIC Participation Status and Income. J Acad Nutr Diet. 2020. 120:2032-2038.e1 | Outcome