# Appendix 2-a Literature search strategy for the rapid review on income and HEI

Database: PubMed

Vendor: National Library of Medicine

Date of Search: 5/11/2021

Limits Used: Filters: Language English Publication Dates 2008 - 2021

Total = 4,718

Search # | Concept | Search String | N
#1 | Income | (“Socioeconomic Factors”[Mesh] OR socioeconomic*[tiab] OR socio-economic*[tiab] OR “social factor*”[tiab] OR “social condition*”[tiab] OR poverty[tiab] OR “Residence Characteristics”[Mesh] OR “Vulnerable Populations”[Mesh] OR “vulnerable population*”[tiab] OR “underserved population*”[tiab] OR “disadvantaged population*”[tiab] OR “Income”[Mesh] OR income*[tiab] OR “Race Factors”[Mesh] OR “race factor*”[tiab] OR “Ethnic Groups”[Mesh] OR “ethnic group*”[tiab] OR “ethnic population*”[tiab] OR “Cross-Cultural Comparison”[Mesh] OR “cross-cultural”[tiab] OR transcultural[tiab] OR “Cultural Characteristics”[Mesh] OR “cultural characteristic*”[tiab] OR “Cultural Diversity”[Mesh] OR “culturally diverse”[tiab] OR “Food Supply”[Mesh] OR “food desert*”[tiab] OR “food insecurit*”[tiab] OR “food environment*”[tiab] OR “food access”[tiab] OR “corner store*”[tiab] OR bodega*[tiab] OR “food cooperative*”[tiab] OR “food store*”[tiab] OR “food market*”[tiab] OR grocer*[tiab] OR supermarket*[tiab] OR “convenience store*”[tiab] OR “food outlet*”[tiab] OR “farmers market*”[tiab] OR Urban[tiab] OR Rural[tiab] OR neighborhood[tiab] OR “Census tract”[tiab] OR “census block”[tiab] OR “food assistance”[MeSH Terms] OR “food assistance”[Tiab]) | 1,087,878
#2 | Dietary Patterns | (“dietary pattern*”[tiab] OR “diet pattern*”[tiab] OR “eating pattern*”[tiab] OR “food pattern*”[tiab] OR “diet quality”[tiab] OR “dietary quality”[tiab] OR “diet divers*”[tiab] OR “dietary divers*”[tiab] OR “diet variety”[tiab] OR “dietary variety”[tiab] OR “varied diet”[tiab] OR “dietary guideline*”[tiab] OR “dietary recommendation*”[tiab] OR “dietary intake*”[tiab] OR “eating style*”[tiab] OR “Diet, Mediterranean”[Mesh] OR “Mediterranean Diet*”[tiab] OR “Dietary Approaches To Stop Hypertension”[Mesh] OR “Dietary Approaches To Stop Hypertension Diet*”[tiab] OR “DASH diet*”[tiab] OR “Diet, Gluten-Free”[Mesh] OR “Gluten Free diet*”[tiab] OR “prudent diet*”[tiab] OR “Diet, Paleolithic”[Mesh] OR “Paleolithic Diet*”[tiab] OR “Diet, Vegetarian”[Mesh] OR “vegetarian diet*”[tiab] OR “vegan diet*”[tiab] OR “Diet, Healthy”[Mesh] OR “plant based diet*”[tiab] OR “Diet, Western”[Mesh] OR “western diet*”[tiab] OR “Nordic Diet*”[tiab] OR “Diet, Fat-Restricted”[Mesh] OR “Diet, High-Fat”[Mesh] OR “high-fat diet*”[tiab] OR “low fat diet*”[tiab] OR ((“Guideline Adherence”[Mesh] OR “guideline adherence*”[tiab])AND (diet[tiab] OR dietary[tiab] OR food[tiab] OR beverage*[tiab] OR nutrition*[tiab])) OR “diet score*”[tiab] OR “diet quality score*”[tiab] OR “diet quality index*”[tiab] OR kidmed[tiab] OR “diet index*”[tiab] OR “dietary index*”[tiab] OR “food score*”[tiab] OR MedDietScore[tiab] OR “healthy eating index”[tiab] ) | 113,841
#4 | Publication, Geography, and species excludes | #1 AND #2 NOT; (letter[ptyp] OR editorial[ptyp] OR comment[ptyp] OR news[ptyp] OR “Congress”[Publication Type] OR “Consensus Development Conference”[Publication Type] OR editorial[tiab] OR commentary[tiab] OR “conference abstract*”[tiab] OR “systematic review*”[ti] OR “meta-analysis”[ptyp] OR “meta-analysis”[ti] OR “meta-analyses”[ti] OR “Review”[Publication Type] OR “Systematic Review”[Publication Type] OR “conference proceeding*”[tiab] OR “retracted publication”[ptyp] OR “retraction of publication”[ptyp] OR “retraction of publication”[tiab] OR “retraction notice”[ti] OR “retracted publication”[tiab] OR “Published Erratum”[Publication Type] OR corrigenda[tiab] OR corrigendum[tiab] OR errata[tiab] OR erratum[tiab] OR protocol[ti] OR protocols[ti] OR “case report”[ti] OR “case series”[ti] OR “Case Reports”[Publication Type]); NOT; (“Developing Countries”[Mesh] OR “developing countr*” OR “Under Developed Nation*” OR “low income countr*” OR “middle income countr*”OR “low-middle-income countr*” OR LMIC[tiab] OR “Europe”[Mesh] OR “Australia”[Mesh] OR “Asia”[Mesh] OR “Africa”[Mesh] OR “Mexico”[Mesh] OR “Islands”[Mesh] OR “Central America”[Mesh] OR “Latin America”[Mesh] OR “South America”[Mesh]); NOT; (“Animals”[Mesh] NOT; (“Animals”[Mesh] AND “Humans”[Mesh]); ) | 6,174
#6 | Filters | Filters: Language: English; Publication Dates: 2008-2021 | 4,718

Database: Business Source Premier

Vendor: EBSCO

Date of Search: 5/11/2021

Limits Used: Scholarly (Peer Reviewed) Journals; Published Date: 20080101-20211231; Document Type: Article; Language: English

Total = 1,044

Search # | Concept | Search String | N
#1 | Income | (DE “SOCIOECONOMIC factors”) OR socioeconomic* OR socio-economic* OR “social factor*” OR “social condition*” OR (DE “POVERTY”) OR poverty OR “vulnerable population*” OR “underserved population*” OR “disadvantaged population*” OR (DE “INCOME”) OR income* OR “race factor*” OR (DE “ECONOMIC conditions of ethnic groups”) OR “ethnic group*” OR “ethnic population*” OR “cross-cultural” OR transcultural OR “cultural characteristic*” OR “culturally diverse” OR (DE “FOOD supply”) OR “food desert*” OR “food insecurit*” OR “food environment*” OR “food access” OR “corner store*” OR bodega* OR DE “FOOD cooperatives” OR “food cooperative*” OR “food store*” OR “food market*” OR (DE “GROCERY shopping”) OR (DE “GROCERY industry”) OR grocer* OR (DE “SUPERMARKETS”) OR supermarket* OR (DE “CONVENIENCE stores”) OR “convenience store*” OR “food outlet*” OR (DE “FARMERS’ markets”) OR “farmers market*”OR (DE “METROPOLITAN areas”) OR Urban OR Rural OR neighborhood OR “Census tract” OR “census block” OR “food assistance” | 1,403,085
#2 | Dietary Patterns | “dietary pattern*” OR “diet pattern*” OR “eating pattern*” OR “food pattern*” OR “diet quality” OR “dietary quality” OR “diet divers*” OR “dietary divers*”OR “diet variety” OR “dietary variety” OR “varied diet” OR “dietary guideline*” OR “dietary recommendation*” OR “dietary intake*” OR “eating style*” OR “Mediterranean Diet*” OR “Dietary Approaches To Stop Hypertension” OR “DASH diet*” OR “Gluten Free diet*” OR “prudent diet*” OR “Paleolithic Diet*” OR “vegetarian diet*” OR “vegan diet*” OR “healthy diet” OR “plant based diet*” OR “western diet*” OR “Nordic Diet*” OR “high-fat diet*”OR “low fat diet*”OR (“guideline adherence*” AND (diet OR dietary OR food OR beverage* OR nutrition*)) OR “diet score*” OR “diet quality score*” OR “diet quality index*” OR kidmed OR “diet index*” OR “dietary index*” OR “food score*” OR “Med Diet Score” OR “healthy eating index” | 13,149
#3 | #1 AND #2 | | 3,225
#4 | Filters | Limiters - Scholarly (Peer Reviewed) Journals; Published Date: 20080101-20211231; Document Type: Article; Language: English | 1,044

Database: Web of Science: Core Collection

Vendor: Clarivate Analytics

Date of Search: 5/11/2021

Limits Used: Years: 2008-2021; Publication Types: Articles, Early Access; Language: English

Total = 7,300

Search # | Concept | Search String | N
#1 | Income | TS=(socioeconomic* OR socio-economic* OR “social factor*” OR “social condition*” OR poverty OR “residence characteristics” OR “vulnerable population*” OR “underserved population*” OR “disadvantaged population*” OR income* OR “race factor*” OR “ethnic group*” OR “ethnic population*” OR “cross-cultural” OR transcultural OR “cultural characteristic*” OR “culturally diverse” OR “food desert*” OR “food insecurit*” OR “food environment*” OR “food access” OR “corner store*” OR bodega* OR “food cooperative*” OR “food store*” OR “food market*” OR grocer* OR supermarket* OR “convenience store*” OR “food outlet*” OR “farmers market*” OR Urban OR Rural OR neighborhood OR “Census tract” OR “census block” OR “food assistance”) | 1,036,318
#2 | Dietary Patterns | TS= (“dietary pattern*” OR “diet pattern*” OR “eating pattern*” OR “food pattern*” OR “diet quality” OR “dietary quality” OR “diet divers*” OR “dietary divers*” OR “diet variety” OR “dietary variety” OR “varied diet” OR “dietary guideline*” OR “dietary recommendation*” OR “dietary intake*” OR “eating style*” OR “Mediterranean Diet*” OR “Dietary Approaches To Stop Hypertension” OR “DASH diet*” OR “Gluten Free diet*” OR “prudent diet*” OR “Paleolithic Diet*” OR “vegetarian diet*” OR “vegan diet*” OR “healthy diet” OR “plant based diet*” OR “western diet*” OR “Nordic Diet*” OR “high-fat diet*” OR “low fat diet*” OR (“guideline adherence*” AND (diet OR dietary OR food OR beverage* OR nutrition*)) OR “diet score*” OR “diet quality score*” OR “diet quality index*” OR kidmed OR “diet index*” OR “dietary index*” OR “food score*” OR “Med Diet Score” OR “healthy eating index”) | 122,259
#3 | #1 AND #2 | | 11,878
#4 | Non-United States Excludes | CU=(“developing countr*” OR “under developed nation*” OR “low income countr*” OR “middle income countr*” OR “low-middle income countr*” OR LMIC; OR Europe OR Australia OR Asia OR Africa OR Mexico OR Islands OR “Central America” OR “Latin America” OR “South America”) | 2,040,699
#5 | #3 NOT #4 | | 10,403
#6 | Publication Excludes | TS=(editorial OR commentary OR “conference abstract*” OR “conference proceeding*”[tiab] OR “retraction of publication” OR “retracted publication” OR corrigenda[tiab] OR corrigendum[tiab] OR errat a OR erratum OR “case reports” ) OR TI=(“systematic review*” OR “meta-analysis”; OR “meta analyses” OR protocol OR protocols; OR “retraction notice” OR “case report” OR; “case series”) | 710,063
#7 | #5 NOT #6 | | 10,151
#8 | | Years: 2008-2021; Publication Types: Articles, Early Access; Language: English | 7,300

## Grey Literature Search

### Google Scholar

Google Scholar’s search has a character limit of 256. To accommodate all of the unique terms in this search strategy, the search has been split and run as three searches.

#### Search A

(Income OR resources OR poverty OR socioeconomic OR urban OR neighborhood) AND (“dietary pattern” OR “food pattern” OR “diet quality” OR “dietary diversity” OR “diet variety” OR “dietary guideline” OR “dietary recommendation” OR “dietary intake” OR “eating style”)

Limits: Date Published: 2008-2021;

Date Searched: 5/17/2021

Results: 80, limited to 8 pages

#### Search B

(Income OR resources OR poverty OR socioeconomic OR urban OR neighborhood)AND (“Mediterranean Diet” OR “Dietary Approaches To Stop Hypertension” OR “DASH diet” OR “western diet” OR “Nordic diet”)

Limits: Date Published: 2008-2021;

Date Searched: 5/17/2021

Results: 20, limited to 2 pages

#### Search C

(Income OR resources OR poverty OR socioeconomic OR urban OR neighborhood) AND (“Gluten Free diet” OR “prudent diet” OR “Paleolithic Diet” OR “vegetarian diet” OR “vegan diet” OR “healthy diet” OR “plant based diet”)

Limits: Date Published: 2008-2021;

Date Searched: 5/17/2021

Results: 20, limited to 2 pages

Total: 120

### Google

Google limits queries to 32 words (from Google notification, 5/17/21). To accommodate all of the unique terms in this search strategy, the search has been split and run as three searches.

#### Search A

site:.gov AND (Income OR resources OR poverty OR socioeconomic OR urban OR neighborhood) AND (“dietary pattern” OR “food pattern” OR “diet quality” OR “dietary diversity” OR “diet variety” OR “dietary guideline” OR “dietary recommendation” OR “dietary intake” OR “eating style”)

Limits: Similar results omitted

Date Searched: 5/17/2021

Results: 12

#### Search B

site:.gov AND (Income OR resources OR poverty OR socioeconomic OR urban OR neighborhood) AND (“Mediterranean Diet” OR “Dietary Approaches To Stop Hypertension” OR “DASH diet” OR “western diet” OR “Nordic diet”)

Limits: Similar results omitted

Date Searched: 5/17/2021

Results: 10, limited to 1 page

#### Search C

site:.gov AND (Income OR resources OR poverty OR socioeconomic OR urban OR neighborhood) AND (“Gluten Free diet” OR “prudent diet” OR “Paleolithic Diet” OR “vegetarian diet” OR “vegan diet” OR “healthy diet” OR “plant based diet”)

Limits: Similar results omitted

Date Searched: 5/17/2021

Results: 20, limited to 2 pages

Total: 42

### AgEcon

Any of the words: Income resources poverty socioeconomic urban neighborhood

AND

Any of the words: “dietary pattern” “food pattern” “diet quality” “dietary diversity” “diet variety” “dietary guideline” “dietary recommendation” “dietary intake” “eating style” “Mediterranean Diet” “Dietary Approaches To Stop Hypertension” “DASH diet” “western diet” “Nordic diet” OR “Gluten Free diet” “prudent diet” “Paleolithic Diet” “vegetarian diet” “vegan diet” “healthy diet” “plant based diet”

Limits: added since 2008

Date Searched: 5/17/2021

Results: 50, results are limited to 5 pages

Results after Deduplication:

- Google Scholar: 120
- Google: 40
- AgEcon: 59