# Appendix 1-b Excluded articles for the rapid review on income and food prices

The following table lists the articles excluded after full-text screening for this rapid review question. At least 1 reason for exclusion is provided for each article, though this may not reflect all possible reasons. Information about articles excluded after title and abstract screening is available upon request.

| Citation | Reason for exclusion
1. | CONSUMER EXPENDITURES -2019. 2020. | Outcome
2. | Vermont Basic Needs Budgets and Livable Wage. 2021. | Study Design
3. | LONG-TERM BENEFITS OF THE SUPPLEMENTAL NUTRITION ASSISTANCE PROGRAM. 2015. | Outcome
4. | Milwaukee Fresh Food Access Report. 2019. 86. | Outcome
5. | USDA Food Plans: Cost of Food Reports (monthly reports) \| USDA-FNS. 2021. | Intervention/Exposure
6. | NC DHHS: Food and Nutrition Services Food Stamps. 2021. | Study Design
7. | Ollinger, M, Guthrie,. Volume of Purchases and Regional Location Have Strong Effects on Food Costs for School Meals. 2019. April 2019. doi:10.22004/ag.econ.302701. | Intervention/Exposure
8. | Aaron, GJ, Keim, NL, Drewnowski, A, Townsend, MS. Estimating dietary costs of low-income women in California: a comparison of 2 approaches. Am J Clin Nutr. 2013. 97:835-41. doi:10.3945/ajcn.112.044453. | Intervention/Exposure
9. | Aggarwal, A, Cook, AJ, Jiao, J, Seguin, RA, Vernez Moudon, A, Hurvitz, PM, Drewnowski, A. Access to supermarkets and fruit and vegetable consumption. Am J Public Health. 2014. 104:917-23. doi:10.2105/ajph.2013.301763. | Outcome
10. | Aggarwal, A, Monsivais, P, Cook, AJ, Drewnowski, A. Does diet cost mediate the relation between socioeconomic position and diet quality? Eur J Clin Nutr. 2011. 65:1059-66. doi:10.1038/ejcn.2011.72. | Outcome
11. | Aggarwal, A, Monsivais, P, Cook, AJ, Drewnowski, A. Positive attitude toward healthy eating predicts higher diet quality at all cost levels of supermarkets. J Acad Nutr Diet. 2014. 114:266-72. doi:10.1016/j.jand.2013.06.006. | Outcome
12. | Aggarwal, A, Monsivais, P, Drewnowski, A. Nutrient intakes linked to better health outcomes are associated with higher diet costs in the US. PLoS One. 2012. 7:e37533. doi:10.1371/journal.pone.0037533. | Outcome
13. | Aggarwal, A, Rehm, CD, Monsivais, P, Drewnowski, A. Importance of taste, nutrition, cost and convenience in relation to diet quality: Evidence of nutrition resilience among US adults using National Health and Nutrition Examination Survey (NHANES) 2007-2010. Prev Med. 2016. 90:184-92. doi:10.1016/j.ypmed.2016.06.030. | Intervention/Exposure
14. | Alemu, R, Block, SA, Headey, D, Bai, Y, Masters, WA. Why are nutritious foods so expensive? Economic development and the cost of nutritious diets. 2018. 32. doi:10.22004/ag.econ.281163. | Country
15. | Allcott, H, Diamond, R, Dubé, J-P, Handbury, J, Rahko vs.ky, I, Schnell, M. Food Deserts and the Causes of Nutritional Inequality. Quarterly Journal of Economics. 2019. 134:1793-1844. doi:10.1093/qje/qjz015. | Intervention/Exposure
16. | Alston, JM, Pardey, PG. Agricultural R&D, Food Prices, Poverty and Malnutrition Redux. 2014. 45. doi:10.22004/ag.econ.162413. | Study Design
17. | Anderson, K, Cockburn, J, Martin, W. Agricultural price distortions, inequality, and poverty. 2010. | Outcome
18. | Andrews, M, Kantar, LS, Lino, M, Ripplinger, D. Using the USDA’s Thrifty Food Plan to assess food availability and affordability. 24. 2001. 45-53. | Comparator
19. | Andreyeva, T, Luedicke, J, Middleton, AE, Long, MW, Schwartz, MB. Positive influence of the revised Special Supplemental Nutrition Program for Women, Infants, and Children food packages on access to healthy foods. J Acad Nutr Diet. 2012. 112:850-8. doi:10.1016/j.jand.2012.02.019. | Intervention/Exposure
20. | Anekwe, TD, Rahko vs.ky, I. The association between food prices and the blood glucose level of US adults with type 2 diabetes. Am J Public Health. 2014. 104:678-85. doi:10.2105/ajph.2013.301661. | Intervention/Exposure
21. | Appelhans, BM, Milliron, BJ, Woolf, K, Johnson, TJ, Pagoto, SL, Schneider, KL, Whited, MC, Ventrelle, JC. Socioeconomic status, energy cost, and nutrient content of supermarket food purchases. Am J Prev Med. 2012. 42:398-402. doi:10.1016/j.amepre.2011.12.007. | Outcome
22. | Ard, JD, Fitzpatrick, S, Desmond, RA, Sutton, BS, Pisu, M, Allison, DB, Franklin, F, Baskin, ML. The impact of cost on the availability of fruits and vegetables in the homes of schoolchildren in Birmingham, Alabama. Am J Public Health. 2007. 97:367-72. doi:10.2105/ajph.2005.080655. | Intervention/Exposure
23. | Askelson, NM, Meier, C, Baquero, B, Friberg, J, Montgomery, D, Hradek, C. Understanding the Process of Prioritizing Fruit and Vegetable Purchases in Families With Low Incomes: “A Peach May Not Fill You Up as Much as Hamburger”. Health Educ Behav. 2018. 45:817-823. doi:10.1177/1090198117752790. | Outcome
24. | Basu, S, Wimer, C, Seligman, H. Moderation of the Relation of County-Level Cost of Living to Nutrition by the Supplemental Nutrition Assistance Program. Am J Public Health. 2016. 106:2064-2070. doi:10.2105/ajph.2016.303439. | Intervention/Exposure
25. | Beheshti, R, Igusa, T, Jones-Smith, J. Simulated Models Suggest That Price per Calorie Is the Dominant Price Metric That Low-Income Individuals Use for Food Decision Making. J Nutr. 2016. 146:2304-2311. doi:10.3945/jn.116.235952. | Outcome
26. | Berkowitz, SA, Basu, S, Meigs, JB, Seligman, HK. Food Insecurity and Health Care Expenditures in the United States, 2011-2013. Health Serv Res. 2018. 53:1600-1620. doi:10.1111/1475-6773.12730. | Outcome
27. | Bertoni, AG, Foy, CG, Hunter, JC, Quandt, SA, Vitolins, MZ, Whitt-Glover, MC. A multilevel assessment of barriers to adoption of Dietary Approaches to Stop Hypertension (DASH) among African Americans of low socioeconomic status. J Health Care Poor Underserved. 2011. 22:1205-20. doi:10.1353/hpu.2011.0142. | Comparator
28. | Beydoun, MA, Fanelli-Kuczmarski, MT, Allen, A, Beydoun, HA, Popkin, BM, Evans, MK, Zonderman, AB. Monetary Value of Diet Is Associated with Dietary Quality and Nutrient Adequacy among Urban Adults, Differentially by Sex, Race and Poverty Status. PLoS One. 2015. 10:e0140905. doi:10.1371/journal.pone.0140905. | Intervention/Exposure
29. | Beydoun, MA, Nkodo, A, Fanelli-Kuczmarski, MT, Maldonado, AI, Beydoun, HA, Popkin, BM, Evans, MK, Zonderman, AB. Longitudinal Associations between Monetary Value of the Diet, DASH Diet Score and the Allostatic Load among Middle-Aged Urban Adults. Nutrients. 2019. 11:doi:10.3390/nu11102360. | Outcome
30. | Blecher, E, Liber, AC, Drope, JM, Nguyen, B, Stoklosa, M. Global Trends in the Affordability of Sugar-Sweetened Beverages, 1990-2016. Preventing Chronic Disease. 2017. 14:doi:10.5888/pcd14.160406. | Comparator
31. | Blisard, N, Stewart, H, Jolliffe, D. Low-income households’ expenditures on fruits and vegetables. 2004. | Other Exclude
32. | Blisard, N, Smallwood, D, Lutz, S. Food Cost Indexes for Low-Income Households and the General Population. 1999. 29. doi:10.22004/ag.econ.156813. | Intervention/Exposure
33. | Blisard, N, Stewart, H. How Low-Income Households Allocate Their Food Budget Relative to the Cost of the Thrifty Food Plan. 2006. 29. doi:10.22004/ag.econ.7239. | Comparator
34. | Blisard, N, Stewart, H. Food Spending in American Households, 2003-04. 2007. 108. doi:10.22004/ag.econ.59033. | Comparator
35. | Blitstein, JL, Snider, J, Evans, WD. Perceptions of the food shopping environment are associated with greater consumption of fruits and vegetables. Public Health Nutr. 2012. 15:1124-9. doi:10.1017/s1368980012000523. | Outcome
36. | Bluthenthal, RN, Cohen, DA, Farley, TA, Scribner, R, Beighley, C, Schonlau, M, Robinson, PL. Alcohol availability and neighborhood characteristics in Los Angeles, California and southern Louisiana. J Urban Health. 2008. 85:191-205. doi:10.1007/s11524-008-9255-1. | Outcome
37. | Boehm, R, Ver Ploeg, M, Wilde, PE, Cash, SB. Greenhouse gas emissions, total food spending and diet quality by share of household food spending on red meat: results from a nationally representative sample of US households. Public Health Nutr. 2019. 22:1794-1806. doi:10.1017/s136898001800407x. | Outcome
38. | Breck, A, Kiszko, KM, Abrams, C, Elbel, B. Spending at mobile fruit and vegetable carts and using SNAP benefits to pay, Bronx, New York, 2013 and 2014. Prev Chronic Dis. 2015. 12:E87. doi:10.5888/pcd12.140542. | Outcome
39. | Breyer, B, Voss-Andreae, A. Food mirages: geographic and economic barriers to healthful food access in Portland, Oregon. Health Place. 2013. 24:131-9. doi:10.1016/j.healthplace.2013.07.008. | Intervention/Exposure
40. | Brinkley, C, Chrisinger, B, Hillier, A. Tradition of healthy food access in low-income neighborhoods: Price and variety of curbside produce vending compared to conventional retailers. J Agric Food Syst Community Dev. 2013. 4:155-169. doi:10.5304/jafscd.2013.041.011. | Intervention/Exposure
41. | Bronchetti, ET, Christensen, G, Hoynes, HW. Local food prices, SNAP purchasing power, and child health. J Health Econ. 2019. 68:102231. doi:10.1016/j.jhealeco.2019.102231. | Intervention/Exposure
42. | Brown, C. Consumers’ preferences for locally produced food: A study in southeast Missouri. American Journal of Alternative Agriculture. 2003. 18:213-224. doi:10.1079/ajaa200353. | Comparator
43. | Budd, N, Cuccia, A, Jeffries, JK, Prasad, D, Frick, KD, Powell, L, Katz, FA, Gittelsohn, J. B’More Healthy: Retail Rewards--design of a multi-level communications and pricing intervention to improve the food environment in Baltimore City. BMC Public Health. 2015. 15:283. doi:10.1186/s12889-015-1616-6. | Study Design
44. | Burns, C, Cook, K, Mavoa, H. Role of expendable income and price in food choice by low income families. Appetite. 2013. 71:209-17. doi:10.1016/j.appet.2013.08.018. | Country
45. | Buszkiewicz, J, House, C, Aggarwal, A, Long, M, Drewnowski, A, Otten, JJ. The Impact of a City-Level Minimum Wage Policy on Supermarket Food Prices by Food Quality Metrics: A Two-Year Follow Up Study. Int J Environ Res Public Health. 2019. 16:doi:10.3390/ijerph16010102. | Intervention/Exposure
46. | Byker Shanks, C, Ahmed, S, Smith, T, Houghtaling, B, Jenkins, M, Margetts, M, Schultz, D, Stephens, L. Availability, Price, and Quality of Fruits and Vegetables in 12 Rural Montana Counties, 2014. Prev Chronic Dis. 2015. 12:E128. doi:10.5888/pcd12.150158. | Outcome
47. | Cakir, M, Beatty, TKM, Boland, MA, Park, TA, Snyder, S, Wang, YH. SPATIAL AND TEMPORAL VARIATION IN THE VALUE OF THE WOMEN, INFANTS, AND CHILDREN PROGRAM’S FRUIT AND VEGETABLE VOUCHER. American Journal of Agricultural Economics. 2018. 100:691-706. doi:10.1093/ajae/aay002. | Intervention/Exposure
48. | Canto, Amber, Brown, LE, Deller, SC. Rural Poverty, Food Access, and Public Health Outcomes. 2014. 29:5. doi:10.22004/ag.econ.182113. | Comparator
49. | Carlson, A, Page, E, Mentzer RM. USDA’s Purchase to Plate Price Tool Estimates Food Costs for National Food Intake Data. 2020. 2020:doi:10.22004/ag.econ.307281. | Comparator
50. | Carnahan, LR, Zimmermann, K, Peacock, NR. What Rural Women Want the Public Health Community to Know About Access to Healthful Food: A Qualitative Study, 2011. Prev Chronic Dis. 2016. 13:E57. doi:10.5888/pcd13.150583. | Intervention/Exposure
51. | Caspi, CE, Pelletier, JE, Harnack, LJ, Erickson, DJ, Lenk, K, Laska, MN. Pricing of Staple Foods at Supermarkets versus Small Food Stores. Int J Environ Res Public Health. 2017. 14:doi:10.3390/ijerph14080915. | Comparator
52. | Caswell, JA, Yaktine, AL, On Examination of the Adequacy of Food Resources, Snap Allotments, Committee, Board, Food, Nutrition, On National Statistics, Committee, Of Medicine, Institute, Council, National Research. Individual, Household, and Environmental Factors Affecting Food Choices and Access. Supplemental Nutrition Assistance Program: Examining the Evidence to Define Benefit Adequacy. 2013. | Study Design
53. | Cavanaugh, E, Mallya, G, Brensinger, C, Tierney, A, Glanz, K. Nutrition environments in corner stores in Philadelphia. Prev Med. 2013. 56:149-51. doi:10.1016/j.ypmed.2012.12.007. | Comparator
54. | Cerin, E, Frank, LD, Sallis, JF, Saelens, BE, Conway, TL, Chapman, JE, Glanz, K. From neighborhood design and food options to residents’ weight status. Appetite. 2011. 56:693-703. doi:10.1016/j.appet.2011.02.006. | Intervention/Exposure
55. | Chea, M, Mobley, AR. Factors Associated with Identification and Consumption of Whole-Grain Foods in a Low-Income Population. Curr Dev Nutr. 2019. 3:nzz064. doi:10.1093/cdn/nzz064. | Intervention/Exposure
56. | Chen, D, Jaenicke, EC, Volpe, RJ. Food Environments and Obesity: Household Diet Expenditure Versus Food Deserts. Am J Public Health. 2016. 106:881-8. doi:10.2105/ajph.2016.303048. | Outcome
57. | Choi, HJ, Wohlgenant, MK, Zheng, XY. Household-Level Welfare Effects of Organic Milk Introduction. American Journal of Agricultural Economics. 2013. 95:1009-1028. doi:10.1093/ajae/aat021. | Outcome
58. | Chouinard, HH, Davis, DE, LaFrance, JT, Perloff, JM. Milk Marketing Order Winners and Losers. Applied Economic Perspectives and Policy. 2010. 32:59-76. doi:10.1093/aepp/ppp002. | Intervention/Exposure
59. | Clauson, AL. Despite Higher Food Prices, Percent of U.S. Income Spent on Food Remains Constant. 2008. 1. doi:10.22004/ag.econ.124033. | Comparator
60. | Cliff, BQ, Townsend, T, Wolfson, JA. Examining Household Changes in Produce Purchases Among New Parents. J Nutr Educ Behav. 2019. 51:798-805. doi:10.1016/j.jneb.2019.04.010. | Outcome
61. | Connell, CL, Zoellner, JM, Yadrick, MK, Chekuri, SC, Crook, LB, Bogle, ML. Energy density, nutrient adequacy, and cost per serving can provide insight into food choices in the lower Mississippi Delta. J Nutr Educ Behav. 2012. 44:148-53. doi:10.1016/j.jneb.2011.02.003. | Intervention/Exposure
62. | Coughenour, C, Bungum, TJ, Regalado, MN. Healthy Food Options at Dollar Discount Stores Are Equivalent in Quality and Lower in Price Compared to Grocery Stores: An Examination in Las Vegas, NV. Int J Environ Res Public Health. 2018. 15:doi:10.3390/ijerph15122773. | Intervention/Exposure
63. | Crandall, PG, Seideman, S, Ricke, SC, O’Bryan, CA, Fanatico, AF, Rainey, R. Organic poultry: Consumer perceptions, opportunities, and regulatory issues. Journal of Applied Poultry Research. 2009. 18:795-802. doi:10.3382/japr.2009-00025. | Study Design
64. | Damon, AL, King, RP, Leibtag, E. First of the month effect: Does it apply across food retail channels? Food Policy. 2013. 41:18-27. doi:10.1016/j.foodpol.2013.04.005. | Outcome
65. | Daniel, C. Is healthy eating too expensive?: How low-income parents evaluate the cost of food. Soc Sci Med. 2020. 248:112823. doi:10.1016/j.socscimed.2020.112823. | Comparator
66. | Darmon, N, Lacroix, A, Muller, L, Ruffieux, B. Food price policies improve diet quality while increasing socioeconomic inequalities in nutrition. Int J Behav Nutr Phys Act. 2014. 11:66. doi:10.1186/1479-5868-11-66. | Country
67. | Darmon, Nicole, Lacroix, Anne, Muller, Laurent, Ruffieux, Bernard. Food price policies improve diet quality while increasing socioeconomic inequalities in nutrition. International Journal of Behavioral Nutrition and Physical Activity. 2014. 11:1-12. | Country
68. | Davis, CG, Blayney, DP, Yen, ST, Cooper, J. An analysis of at-home demand for ice cream in the United States. J Dairy Sci. 2009. 92:6210-6. doi:10.3168/jds.2009-2536. | Outcome
69. | Davis, DE. Prices Dominate Interstate Variation in WIC Food Costs. 2005. 1. doi:10.22004/ag.econ.130597. | Comparator
70. | DiSantis, KI, Grier, SA, Oakes, JM, Kumanyika, SK. Food prices and food shopping decisions of black women. Appetite. 2014. 77:104-12. doi:10.1016/j.appet.2014.02.016. | Outcome
71. | DiSantis, KI, Grier, SA, Odoms-Young, A, Baskin, ML, Carter-Edwards, L, Young, DR, Lassiter, V, Kumanyika, SK. What “price” means when buying food: insights from a multisite qualitative study with Black Americans. Am J Public Health. 2013. 103:516-22. doi:10.2105/ajph.2012.301149. | Comparator
72. | Dong, D, Lin, B-H. Price Reductions Have Little Effect on Fruits and Vegetable Consumption by Low-Income Americans. 2009. 1. doi:10.22004/ag.econ.124213. | Comparator
73. | Dong, D, Lin, B-H. Fruit and Vegetable Consumption by Low-Income Americans: Would a Price Reduction Make a Difference? 2009. 17. doi:10.22004/ag.econ.55835. | Outcome
74. | Drewnowski, A. Nutrition Economics: How to Eat Better for Less. J Nutr Sci Vitaminol (Tokyo). 2015. 61 Suppl:S69-71. doi:10.3177/jnsv.61.S69. | Study Design
75. | Drewnowski, A, Aggarwal, A, Hurvitz, PM, Monsivais, P, Moudon, AV. Obesity and supermarket access: proximity or price? Am J Public Health. 2012. 102:e74-80. doi:10.2105/ajph.2012.300660. | Other Exclude
76. | Drewnowski, A, Moudon, AV, Jiao, J, Aggarwal, A, Charreire, H, Chaix, B. Food environment and socioeconomic status influence obesity rates in Seattle and in Paris. International Journal of Obesity. 2014. 38:306-314. doi:10.1038/ijo.2013.97. | Outcome
77. | Drewnowski, Adam, Darmon, Nicole. Food choices and diet costs: an economic analysis. The Journal of nutrition. 2005. 135:900-904. | Study Design
78. | Drichoutis, AC, Lazaridis, Panagiotis. What Influences Tastes? An Analysis of the Determinants of Consumers’ Demand for Tastes in Food. 2009. 09:15. doi:10.22004/ag.econ.93803. | Comparator
79. | Elleby, C. Poverty and Price Transmission. 2014. 14. doi:10.22004/ag.econ.182722. | Comparator
80. | Emond, JA, Madanat, HN, Ayala, GX. Do Latino and non-Latino grocery stores differ in the availability and affordability of healthy food items in a low-income, metropolitan region? Public Health Nutr. 2012. 15:360-9. doi:10.1017/s1368980011001169. | Intervention/Exposure
81. | Ethan, D, Basch, CH, Rajan, S, Samuel, L, Hammond, RN. A comparison of the nutritional quality of food products advertised in grocery store circulars of high- versus low-income New York City zip codes. Int J Environ Res Public Health. 2013. 11:537-47. doi:10.3390/ijerph110100537. | Intervention/Exposure
82. | Ethan, D, Samuel, L, Basch, CH. An analysis of Bronx-based online grocery store circulars for nutritional content of food and beverage products. J Community Health. 2013. 38:521-8. doi:10.1007/s10900-012-9643-z. | Outcome
83. | Fan, LL, Baylis, K, Gundersen, C, Ver Ploeg, M. Does a nutritious diet cost more in food deserts? Agricultural Economics. 2018. 49:587-597. doi:10.1111/agec.12444. | Outcome
84. | Fielding-Singh, P, Wang, J. Table talk: How mothers and adolescents across socioeconomic status discuss food. Soc Sci Med. 2017. 187:49-57. doi:10.1016/j.socscimed.2017.06.016. | Outcome
85. | Finke, MS, Chern, WS, Fox, JJ. Do the Urban Poor Pay More for Food? Issues in Measurement. Advancing the Consumer Interest. 1997. 9:13-17. | Other Exclude
86. | Flint, E, Cummins, S, Matthews, S. Do perceptions of the neighbourhood food environment predict fruit and vegetable intake in low-income neighbourhoods? Health Place. 2013. 24:11-5. doi:10.1016/j.healthplace.2013.07.005. | Outcome
87. | French, MT, Browntaylor, D, Bluthenthal, RN. Price elasticity of demand for malt liquor beer: findings from a US pilot study. Soc Sci Med. 2006. 62:2101-11. doi:10.1016/j.socscimed.2005.10.012. | Outcome
88. | French, SA, Tangney, CC, Crane, MM, Wang, Y, Appelhans, BM. Nutrition quality of food purchases varies by household income: the SHoPPER study. BMC Public Health. 2019. 19:231. doi:10.1186/s12889-019-6546-2. | Outcome
89. | Glanz, K, Sallis, JF, Saelens, BE, Frank, LD. Nutrition Environment Measures Survey in stores (NEMS-S): development and evaluation. Am J Prev Med. 2007. 32:282-9. doi:10.1016/j.amepre.2006.12.019. | Outcome
90. | Glanz, Karen, Basil, Michael, Maibach, Edward, Goldberg, Jeanne, Snyder, DAN. Why Americans eat what they do: taste, nutrition, cost, convenience, and weight control concerns as influences on food consumption. Journal of the American Dietetic Association. 1998. 98:1118-1126. | Outcome
91. | Golan, Elise H, Stewart, Hayden, Kuchler, Fred, Dong, Diansheng. Can low-income Americans afford a healthy diet? 2008. | Comparator
92. | Gordon-Larsen, P, Guilkey, DK, Popkin, BM. An economic analysis of community-level fast food prices and individual-level fast food intake: a longitudinal study. Health Place. 2011. 17:1235-41. doi:10.1016/j.healthplace.2011.07.011. | Outcome
93. | Gorham, G, Dulin-Keita, A, Risica, PM, Mello, J, Papandonatos, G, Nunn, A, Gorham, S, Roberson, M, Gans, KM. Effectiveness of Fresh to You, a Discount Fresh Fruit and Vegetable Market in Low-Income Neighborhoods, on Children’s Fruit and Vegetable Consumption, Rhode Island, 2010-2011. Prev Chronic Dis. 2015. 12:E176. doi:10.5888/pcd12.140583. | Intervention/Exposure
94. | Goryakin, Y, Monsivais, P, Suhrcke, M. Soft drink prices, sales, body mass index and diabetes: Evidence from a panel of low-, middle- and high-income countries. Food Policy. 2017. 73:88-94. doi:10.1016/j.foodpol.2017.09.002. | Intervention/Exposure
95. | Gouri Suresh, SS, Schauder, SA. Income Segregation and Access to Healthy Food. Am J Prev Med. 2020. 59:e31-e38. doi:10.1016/j.amepre.2020.02.009. | Outcome
96. | Govindasamy, Ramu, Purduri, Venkata, Kelley, Kathleen, Simon, JamesE. Influence of Consumer Demographics on the Demand for Locally Grown Ethnic Greens and Herbs Because of Food Miles Concerns: A Logit Model Analysis. 2012. 43:2. doi:10.22004/ag.econ.139446. | Outcome
97. | Grindal, T, Wilde, P, Schwartz, G, Klerman, J, Bartlett, S, Berman, D. Does food retail access moderate the impact of fruit and vegetable incentives for SNAP participants? Evidence from western Massachusetts. Food Policy. 2016. 61:59-69. doi:10.1016/j.foodpol.2016.02.002. | Outcome
98. | Gupta, S, Rose, CM, Buszkiewicz, J, Ko, LK, Mou, J, Cook, A, Aggarwal, A, Drewnowski, A. Characterising percentage energy from ultra-processed foods by participant demographics, diet quality and diet cost: findings from the Seattle Obesity Study (SOS) III. Br J Nutr. 2020. 1-9. doi:10.1017/s0007114520004705. | Outcome
99. | Hagues, R, Stotz, S, Childers, A, Phua, J, Hibbs, J, Murray, D, Lee, JS. Social marketing nutrition education for low-income population. Soc Work Public Health. 2018. 33:317-328. doi:10.1080/19371918.2018.1469065. | Comparator
100. | Han, E, Powell, LM. Effect of food prices on the prevalence of obesity among young adults. Public Health. 2011. 125:129-35. doi:10.1016/j.puhe.2010.11.014. | Intervention/Exposure
101. | Han, Euna, Powell, LM. FAST FOOD PRICES AND ADULT BODY WEIGHT OUTCOMES: EVIDENCE BASED ON LONGITUDINAL QUANTILE REGRESSION MODELS. Contemporary Economic Policy. 2013. 31:528-536. doi:10.1111/j.1465-7287.2012.00322.x. | Outcome
102. | Hanson, GD, Herrmann, RO, Dunn, JW. Determinants of seafood purchase behavior: Consumers, restaurants, and grocery stores. American Journal of Agricultural Economics. 1995. 77:1301-1305. doi:10.2307/1243365. | Study Design
103. | Hanson, KL, Garner, J, Connor, LM, Jilcott Pitts, SB, McGuirt, J, Harris, R, Kolodinsky, J, Wang, W, Sitaker, M, Ammerman, A, Seguin, RA. Fruit and Vegetable Preferences and Practices May Hinder Participation in Community-Supported Agriculture Among Low-Income Rural Families. J Nutr Educ Behav. 2019. 51:57-67. doi:10.1016/j.jneb.2018.08.006. | Comparator
104. | Harwood, EM, Erickson, DJ, Fabian, LE, Jones-Webb, R, Slater, S, Chaloupka, FJ. Effects of communities, neighborhoods and stores on retail pricing and promotion of beer. J Stud Alcohol. 2003. 64:720-6. doi:10.15288/jsa.2003.64.720. | Outcome
105. | Hausman, J, Leibtag, E. Consumer benefits from increased competition in shopping outlets: Measuring the effect of Wal-Mart. Journal of Applied Econometrics. 2007. 22:1157-1177. doi:10.1002/jae.994. | Study Design
106. | Haynes-Maslow, L, Auvergne, L, Mark, B, Ammerman, A, Weiner, BJ. Low-Income Individuals’ Perceptions About Fruit and Vegetable Access Programs: A Qualitative Study. J Nutr Educ Behav. 2015. 47:317-24.e1. doi:10.1016/j.jneb.2015.03.005. | Intervention/Exposure
107. | Haynes-Maslow, L, Parsons, SE, Wheeler, SB, Leone, LA. A qualitative study of perceived barriers to fruit and vegetable consumption among low-income populations, North Carolina, 2011. Prev Chronic Dis. 2013. 10:E34. doi:10.5888/pcd10.120206. | Outcome
108. | Hendrickson, D, Smith, C, Eikenberry, N. Fruit and vegetable access in four low-income food deserts communities in Minnesota. Agriculture and Human Values. 2006. 23:371-383. doi:10.1007/s10460-006-9002-8. | Comparator
109. | Hillier, A, McLaughlin, J, Cannuscio, CC, Chilton, M, Krasny, S, Karpyn, A. The impact of WIC food package changes on access to healthful food in 2 low-income urban neighborhoods. J Nutr Educ Behav. 2012. 44:210-6. doi:10.1016/j.jneb.2011.08.004. | Outcome
110. | Hinrichs, CC. Embeddedness and local food systems: notes on two types of direct agricultural market. Journal of rural studies. 2000. 16:295-303. | Intervention/Exposure
111. | Hirsch, J A, Hillier, A. Exploring the role of the food environment on food shopping patterns in Philadelphia, PA, USA: a semiquantitative comparison of two matched neighborhood groups. International journal of environmental research and public health. 2013. 10:295-313. | Comparator
112. | Hirvonen, K, Bai, Y, Headey, D, Masters, WA. Affordability of the EAT-Lancet reference diet: a global analysis. Lancet Glob Health. 2020. 8:e59-e66. doi:10.1016/s2214-109x(19)30447-4. | Comparator
113. | Hoenink, JC, Beulens, JWJ, Harbers, MC, Boer, JMA, Dijkstra, SC, Nicolaou, M, van der Schouw, YT, Sluijs, I, Verschuren, WMM, Waterlander, W, Mackenbach, JD. To what extent do dietary costs explain socio-economic differences in dietary behavior? Nutr J. 2020. 19:88. doi:10.1186/s12937-020-00608-x. | Country
114. | Hu, A, Acosta, A, McDaniel, A, Gittelsohn, J. Community perspectives on barriers and strategies for promoting locally grown produce from an urban agriculture farm. Health Promot Pract. 2013. 14:69-74. doi:10.1177/1524839911405849. | Comparator
115. | Huang, CL, Lin, BH. A hedonic analysis of fresh tomato prices among regional markets. Review of Agricultural Economics. 2007. 29:783-800. doi:10.1111/j.1467-9353.2007.00387.x. | Outcome
116. | Huang, KS. Nutrient elasticities in a complete food demand system. American Journal of Agricultural Economics. 1996. 78:21-29. doi:10.2307/1243775. | Intervention/Exposure
117. | Huang, KS, Huang, SW. Consumer welfare effects of increased food and energy prices. Applied Economics. 2012. 44:2527-2536. doi:10.1080/00036846.2011.566182. | Outcome
118. | Huang, M-H, Hahn, DE, Jones, Eugene. A SOCIOECONOMIC APPROACH TO ASSESSING PRICE COMPETITION BETWEEN PRIVATE LABELS AND NATIONAL BRANDS: THE CASE OF SHREDDED CHEESE. 2003. 26. doi:10.22004/ag.econ.21993. | Outcome
119. | Ismail, MS, Ver Ploeg, M, Chomitz, VR, Wilde, P. Differences in Food-at-Home Spending for SNAP and Non-SNAP Households Given Geographic Price Variation. J Acad Nutr Diet. 2020. 120:1142-1150.e12. doi:10.1016/j.jand.2019.12.017. | Outcome
120. | Ivanic, MA, Martin, W. Short- and Long-Run Impacts of Food Price Changes on Poverty. Short- and Long-Run Impacts of Food Price Changes on Poverty. . doi:10.1596/1813-9450-7011. | Country
121. | Jetter, KM, Adkins, J, Cortez, S, Hopper, GK, Jr, Shively, V, Styne, DM. Yes We Can: Eating Healthy on a Limited Budget. J Nutr Educ Behav. 2019. 51:268-276. doi:10.1016/j.jneb.2018.12.002. | Intervention/Exposure
122. | Jetter, KM, Cassady, DL. The availability and cost of healthier food alternatives. Am J Prev Med. 2006. 30:38-44. doi:10.1016/j.amepre.2005.08.039. | Comparator
123. | Jetter, KM, Cassady, Diana. EXPLAINING DISPARITIES IN THE COST OF HEALTHIER FOOD. 2004. 17. doi:10.22004/ag.econ.20181. | Study Design
124. | Jiao, J, Moudon, AV, Ulmer, J, Hurvitz, PM, Drewnowski, A. How to identify food deserts: measuring physical and economic access to supermarkets in King County, Washington. Am J Public Health. 2012. 102:e32-9. doi:10.2105/ajph.2012.300675. | Intervention/Exposure
125. | Jilcott, SB, Hurwitz, J, Moore, JB, Blake, C. Qualitative perspectives on the use of traditional and nontraditional food venues among middle- and low-income women in Eastern North Carolina. Ecol Food Nutr. 2010. 49:373-89. doi:10.1080/03670244.2010.507438. | Outcome
126. | Johnson, DS, Rogers, JM, Tan, Lucilla. A Century of Family Budgets in the United States. Monthly Labor Review. 2001. 18. | Outcome
127. | Johnson, JS, Nobmann, ED, Asay, E. Factors related to fruit, vegetable and traditional food consumption which may affect health among Alaska Native People in Western Alaska. Int J Circumpolar Health. 2012. 71:17345. doi:10.3402/ijch.v71i0.17345. | Outcome
128. | Jones, E. An analysis of consumer food shopping behavior using supermarket scanner data: Differences. American Journal of Agricultural Economics. 1997. 79:1437. doi:10.2307/1244358. | Comparator
129. | Jones, E. Consumer demand for carbohydrates: A look across products and income classes. Agribusiness. 1997. 13:599-612. doi:10.1002/(SICI)1520-6297(199711/12)13:6<599::AID-AGR5>3.0.CO;2-Z. | Outcome
130. | Karp, RJ, Wong, G, Orsi, M. Demonstrating Nutrient Cost Gradients: A Brooklyn Case Study. Int J Vitam Nutr Res. 2014. 84:244-51. doi:10.1024/0300-9831/a000210. | Comparator
131. | Kaufman, PR, MacDonald, JM, Lutz, SM, Smallwood, DM. Do the poor pay more for food? Item selection and price differences affect low-income household food costs. 1997. Agricultural Economic Report 759. | Other Exclude
132. | Kaufman, PR. ASSESSMENT OF WIC COST-CONTAINMENT PRACTICES: FOOD ASSISTANCE RESEARCH BRIEF. 2003. 2. doi:10.22004/ag.econ.33855. | Intervention/Exposure
133. | Keim, NL, Forester, SM, Lyly, M, Aaron, GJ, Townsend, MS. Vegetable variety is a key to improved diet quality in low-income women in California. J Acad Nutr Diet. 2014. 114:430-5. doi:10.1016/j.jand.2013.07.026. | Intervention/Exposure
134. | Kern, DM, Auchincloss, AH, Stehr, MF, Roux, AVD, Moore, LV, Kanter, GP, Robinson, LF. Neighborhood Prices of Healthier and Unhealthier Foods and Associations with Diet Quality: Evidence from the Multi-Ethnic Study of Atherosclerosis. Int J Environ Res Public Health. 2017. 14:doi:10.3390/ijerph14111394. | Intervention/Exposure
135. | Kershaw, KN, Klikuszowian, E, Schrader, L, Siddique, J, Van Horn, L, Womack, VY, Zenk, SN. Assessment of the influence of food attributes on meal choice selection by socioeconomic status and race/ethnicity among women living in Chicago, USA: A discrete choice experiment. Appetite. 2019. 139:19-25. doi:10.1016/j.appet.2019.04.003. | Outcome
136. | Khan, R, Misra, K, Singh, V. Will a Fat Tax Work? Marketing Science. 2016. 35:10-26. doi:10.1287/mksc.2015.0917. | Outcome
137. | Khan, T, Powell, LM, Wada, R. Fast food consumption and food prices: evidence from panel data on 5th and 8th grade children. J Obes. 2012. 2012:857697. doi:10.1155/2012/857697. | Outcome
138. | King, RP, Leibtag, ES, Behl, AS. SUPERMARKET CHARACTERISTICS AND OPERATING COSTS IN LOW-INCOME AREAS. 2004. 26. doi:10.22004/ag.econ.20361. | Study Design
139. | Kinsey, JD. The economics of federal food programs: Weighing the costs and benefits - Executive Summary. 2013. 3. doi:10.22004/ag.econ.156194. | Outcome
140. | Kinsey, JD. The economics of federal food programs: Weighing the costs and benefits. 2013. 20. doi:10.22004/ag.econ.156193. | Outcome
141. | Ko, LK, Enzler, C, Perry, CK, Rodriguez, E, Mariscal, N, Linde, S, Duggan, C. Food availability and food access in rural agricultural communities: use of mixed methods. BMC Public Health. 2018. 18:634. doi:10.1186/s12889-018-5547-x. | Outcome
142. | Koelkebeck, KW, Bell, DD, Carey, JB, Anderson, KE, Darre, MJ. Egg marketing in national supermarkets: Products, packaging, and prices - Part 3. Poultry Science. 2001. 80:396-400. doi:10.1093/ps/80.4.396. | Intervention/Exposure
143. | Krebs-Smith, SM, Kantor, LS. Choose a variety of fruits and vegetables daily: understanding the complexities. J Nutr. 2001. 131:487s-501s. doi:10.1093/jn/131.2.487S. | Intervention/Exposure
144. | Krukowski, RA, West, DS, Harvey-Berino, J, Elaine Prewitt, T. Neighborhood impact on healthy food availability and pricing in food stores. J Community Health. 2010. 35:315-20. doi:10.1007/s10900-010-9224-y. | Outcome
145. | Kuhns, A, Levin, D. Retail Food Price Inflation Varies Geographically. 2016. 1. doi:10.22004/ag.econ.244275. | Comparator
146. | Kumcu, A, Volpe, R III. Disaggregated Retail Food Price Indices Using Homescan Data: An Application to Income Levels and SNAP Benefits. 2013. 6. doi:10.22004/ag.econ.150985. | Outcome
147. | Kwon, S-O, Oh, S-Y. Associations of household food insecurity with socioeconomic measures, health status and nutrient intake in low income elderly. Journal of Nutrition and Health. 2007. 40:762-768. | Language
148. | Kyureghian, G, Nayga, RM. FOOD STORE ACCESS, AVAILABILITY, AND CHOICE WHEN PURCHASING FRUITS AND VEGETABLES. American Journal of Agricultural Economics. 2013. 95:1280-1286. doi:10.1093/ajae/aat043. | Outcome
149. | Laraia, BA, Leak, TM, Tester, JM, Leung, CW. Biobehavioral Factors That Shape Nutrition in Low-Income Populations: A Narrative Review. American Journal of Preventive Medicine. 2017. 52:S118-S126. doi:10.1016/j.amepre.2016.08.003. | Study Design
150. | Larsen, K, Gilliland, J. A farmers’ market in a food desert: Evaluating impacts on the price and availability of healthy food. Health Place. 2009. 15:1158-62. doi:10.1016/j.healthplace.2009.06.007. | Country
151. | Larson, NI, Story, MT, Nelson, MC. Neighborhood environments: disparities in access to healthy foods in the US. American journal of preventive medicine. 2009. 36:74-81. e10. | Study Design
152. | Lear, SA, Gasevic, D, Schuurman, N. Association of supermarket characteristics with the body mass index of their shoppers. Nutr J. 2013. 12:117. doi:10.1186/1475-2891-12-117. | Country
153. | Lee, RE, Heinrich, KM, Medina, AV, Regan, GR, Reese-Smith, JY, Jokura, Y, Maddock, JE. A picture of the healthful food environment in two diverse urban cities. Environ Health Insights. 2010. 4:49-60. doi:10.4137/ehi.s3594. | Intervention/Exposure
154. | Leibtag, E. Where you shop matters: Store formats drive variation in retail food prices. Amber Waves. 2005. 3:12-18. | Comparator
155. | Lent, MR, Vander Veur, SS, McCoy, TA, Wojtanowski, AC, Sandoval, B, Sherman, S, Komaroff, E, Foster, GD. A randomized controlled study of a healthy corner store initiative on the purchases of urban, low-income youth. Obesity (Silver Spring). 2014. 22:2494-500. doi:10.1002/oby.20878. | Outcome
156. | Leone, LA, Beth, D, Ickes, SB, Macguire, K, Nelson, E, Smith, RA, Tate, DF, Ammerman, AS. Attitudes Toward Fruit and Vegetable Consumption and Farmers’ Market Usage Among Low-Income North Carolinians. J Hunger Environ Nutr. 2012. 7:64-76. doi:10.1080/19320248.2012.651386. | Intervention/Exposure
157. | Li, Y, Zhang, D, Thapa, JR, Madondo, K, Yi, S, Fisher, E, Griffin, K, Liu, B, Wang, Y, Pagán, JA. Assessing the role of access and price on the consumption of fruits and vegetables across New York City using agent-based modeling. Prev Med. 2018. 106:73-78. doi:10.1016/j.ypmed.2017.10.014. | Outcome
158. | Libman, K. Has New York City fallen into the local trap? Public Health. 2015. 129:310-7. doi:10.1016/j.puhe.2014.12.016. | Outcome
159. | Locher, JL, Ritchie, CS, Roth, DL, Sen, B, Vickers, KS, Vailas, LI. Food choice among homebound older adults: motivations and perceived barriers. J Nutr Health Aging. 2009. 13:659-64. doi:10.1007/s12603-009-0194-7. | Intervention/Exposure
160. | Lopez, E, Lopez, RA. Demand for Differentiated Milk Products: Implications for Price Competition. Agribusiness. 2009. 25:453-465. doi:10.1002/agr.20219. | Intervention/Exposure
161. | Lucan, SC, Barg, FK, Long, JA. Promoters and barriers to fruit, vegetable, and fast-food consumption among urban, low-income African Americans--a qualitative approach. Am J Public Health. 2010. 100:631-5. doi:10.2105/ajph.2009.172692. | Outcome
162. | Lucan, SC, Maroko, AR, Sanon, O, Frias, R, Schechter, CB. Urban farmers’ markets: accessibility, offerings, and produce variety, quality, and price compared to nearby stores. Appetite. 2015. 90:23-30. doi:10.1016/j.appet.2015.02.034. | Intervention/Exposure
163. | Lunsford, J, Brunt, A, Foote, J, Rhee, Y, Strand, M, Segall, M. Analysis of Availability, Quality, and Price of Food Options in Denver, CO Grocery Stores. Journal of hunger & environmental nutrition. 2020. doi:10.1080/19320248.2020.1741482. | Outcome
164. | Lusk, JL, Tonsor, GT. How Meat Demand Elasticities Vary with Price, Income, and Product Category. Applied Economic Perspectives and Policy. 2016. 38:673-711. doi:10.1093/aepp/ppv050. | Outcome
165. | MacNell, L. A geo-ethnographic analysis of low-income rural and urban women’s food shopping behaviors. Appetite. 2018. 128:311-320. doi:10.1016/j.appet.2018.05.147. | Comparator
166. | Mancino, L, Kuchler, F. Demand for Whole-grain Bread Before and After the Release of Dietary Guidelines. Applied Economic Perspectives and Policy. 2012. 34:76-101. doi:10.1093/aepp/ppr035. | Outcome
167. | Marcy, TR, Britton, ML, Harrison, D. Identification of barriers to appropriate dietary behavior in low-income patients with type 2 diabetes mellitus. Diabetes Ther. 2011. 2:9-19. doi:10.1007/s13300-010-0012-6. | Outcome
168. | Martin, KS, Ghosh, D, Page, M, Wolff, M, McMinimee, K, Zhang, M. What role do local grocery stores play in urban food environments? A case study of Hartford-Connecticut. PLoS One. 2014. 9:e94033. doi:10.1371/journal.pone.0094033. | Intervention/Exposure
169. | Martin-Neuninger, R, Ruby, MB. What Does Food Retail Research Tell Us About the Implications of Coronavirus (COVID-19) for Grocery Purchasing Habits? Front Psychol. 2020. 11:1448. doi:10.3389/fpsyg.2020.01448. | Study Design
170. | Masters, MA, Stanek Krogstrand, KL, Eskridge, KM, Albrecht, JA. Race/ethnicity and income in relation to the home food environment in US youth aged 6 to 19 years. J Acad Nutr Diet. 2014. 114:1533-43. doi:10.1016/j.jand.2014.04.023. | Outcome
171. | Mayer, SE, Leone, MP. What money can’t buy: Family income and children’s life chances. 1997. | Study Design
172. | McDowell, DR, Allen-Smith, JE, McLean-Meyinsse, PE. Food expenditures and socioeconomic characteristics: Focus on income class. American Journal of Agricultural Economics. 1997. 79:1444-1451. doi:10.2307/1244359. | Outcome
173. | McGuirt, JT, Huebner, G, Ward, R, Jilcott Pitts, SB. Food and Beverage Options at Highway Rest Areas in North Carolina: A Mixed-Methods Audit and Geospatial Approach. Prev Chronic Dis. 2019. 16:E142. doi:10.5888/pcd16.190129. | Comparator
174. | McGuirt, JT, Pitts, SBJ, Hanson, KL, DeMarco, M, Seguin, RA, Kolodinsky, J, Becot, F, Ammerman, AS. A modified choice experiment to examine willingness to participate in a Community Supported Agriculture (CSA) program among low-income parents. Renewable Agriculture and Food Systems. 2020. 35:140-157. doi:10.1017/s1742170518000364. | Intervention/Exposure
175. | McLaughlin, PW. Specialized Stores Serving WIC Customers in California Improve Food Access Without Raising Food Costs. 2019. May 2019:doi:10.22004/ag.econ.302709. | Intervention/Exposure
176. | McLaughlin, PW, Martinez, S. Specialized Stores Serving Participants in USDA’s Special Supplemental Nutrition Program for Women, Infants, and Children (WIC) Can Reduce Program Food Costs and Increase Food Store Access. 2021. 2020:doi:10.22004/ag.econ.310091. | Comparator
177. | Meade, B, Muhammad, A . The Influence of Income and Prices on Global Dietary Patterns by Country, Age, and Gender. 2017. doi:10.22004/ag.econ.266027. | Comparator
178. | Meyer, BD, Sullivan, JX. Five decades of consumption and income poverty. 2009. | Comparator
179. | Meyer, KA, Guilkey, DK, Ng, SW, Duffey, KJ, Popkin, BM, Kiefe, CI, Steffen, LM, Shikany, JM, Gordon-Larsen, P. Sociodemographic differences in fast food price sensitivity. JAMA Intern Med. 2014. 174:434-42. doi:10.1001/jamainternmed.2013.13922. | Outcome
180. | Monsivais, P, Aggarwal, A, Drewnowski, A. Are socio-economic disparities in diet quality explained by diet cost? J Epidemiol Community Health. 2012. 66:530-5. doi:10.1136/jech.2010.122333. | Outcome
181. | Monsivais, P, Drewnowski, A. Lower-energy-density diets are associated with higher monetary costs per kilocalorie and are consumed by women of higher socioeconomic status. J Am Diet Assoc. 2009. 109:814-22. doi:10.1016/j.jada.2009.02.002. | Outcome
182. | Monsivais, P, Perrigue, MM, Adams, SL, Drewnowski, A. Measuring diet cost at the individual level: a comparison of three methods. Eur J Clin Nutr. 2013. 67:1220-5. doi:10.1038/ejcn.2013.176. | Outcome
183. | Mook, K, Laraia, BA, Oddo, VM, Jones-Smith, JC. Food Security Status and Barriers to Fruit and Vegetable Consumption in Two Economically Deprived Communities of Oakland, California, 2013-2014. Prev Chronic Dis. 2016. 13:E21. doi:10.5888/pcd13.150402. | Outcome
184. | Moore, Latetia V, Diez Roux, Ana V. Associations of neighborhood characteristics with the location and type of food stores. American journal of public health. 2006. 96:325-331. | Outcome
185. | Morland, K, Filomena, S. The utilization of local food environments by urban seniors. Prev Med. 2008. 47:289-93. doi:10.1016/j.ypmed.2008.03.009. | Intervention/Exposure
186. | Morland, K, Wing, S, Roux, AD, Poole, C. Neighborhood characteristics associated with the location of food stores and food service places. American journal of preventive medicine. 2002. 22:23-29. | Outcome
187. | Mulik, K, Haynes-Maslow, L. The Affordability of MyPlate: An Analysis of SNAP Benefits and the Actual Cost of Eating According to the Dietary Guidelines. J Nutr Educ Behav. 2017. 49:623-631.e1. doi:10.1016/j.jneb.2017.06.005. | Intervention/Exposure
188. | Mushi-Brunt, C, Haire-Joshu, D, Elliott, M. Food spending behaviors and perceptions are associated with fruit and vegetable intake among parents and their preadolescent children. J Nutr Educ Behav. 2007. 39:26-30. doi:10.1016/j.jneb.2006.06.004. | Outcome
189. | Neckerman, KM, Lovasi, L, Yousefzadeh, P, Sheehan, D, Milinkovic, K, Baecker, A, Bader, MD, Weiss, C, Lovasi, GS, Rundle, A. Comparing nutrition environments in bodegas and fast-food restaurants. J Acad Nutr Diet. 2014. 114:595-602. doi:10.1016/j.jand.2013.07.007. | Outcome
190. | Nelson, E, Fitzgerald, J, Tefft, N. The distributional impact of a green payment policy for organic fruit. PLoS One. 2019. 14:e0211199. doi:10.1371/journal.pone.0211199. | Outcome
191. | Nelson, JP. Economic and Demographic Factors in U.S. Alcohol Demand: A Growth-Accounting Analysis. Empirical Economics. 1997. 22:83-102. doi:10.1007/BF01188171. | Study Design
192. | Nord, M. Food Spending Declined and Food Insecurity Increased for Middle-Income and Low-Income Households From 2000 to 2007. 2009. 19. doi:10.22004/ag.econ.56627. | Outcome
193. | Nord, M, Hopwood, H. Can Food Stamps Do More to Improve Food Choices? An Economic Perspective--Higher Cost of Food in Some Areas May Affect Food Stamp Households’ Ability To Make Healthy Food Choices. 2007. 4. doi:10.22004/ag.econ.59429. | Comparator
194. | O’Connell, M, Buchwald, DS, Duncan, GE. Food access and cost in American Indian communities in Washington State. J Am Diet Assoc. 2011. 111:1375-9. doi:10.1016/j.jada.2011.06.002. | Intervention/Exposure
195. | Oliveira, Victor. Differences in Per-Person Food Costs for SNAP and WIC Have Widened Over Time. 2014. 1. doi:10.22004/ag.econ.210864. | Comparator
196. | Omar, MA, Coleman, G, Hoerr, S. Healthy eating for rural low-income toddlers: caregivers’ perceptions. J Community Health Nurs. 2001. 18:93-106. doi:10.1207/s15327655jchn1802_03. | Comparator
197. | Onufrak, SJ, Zaganjor, H, Pan, L, Lee-Kwan, SH, Park, S, Harris, DM. Foods and Beverages Obtained at Worksites in the United States. J Acad Nutr Diet. 2019. 119:999-1008. doi:10.1016/j.jand.2018.11.011. | Outcome
198. | Otten, JJ, Buszkiewicz, J, Tang, W, Aggarwal, A, Long, M, Vigdor, J, Drewnowski, A. The Impact of a City-Level Minimum-Wage Policy on Supermarket Food Prices in Seattle-King County. Int J Environ Res Public Health. 2017. 14:doi:10.3390/ijerph14091039. | Intervention/Exposure
199. | Owens, MM, Ray, LA, MacKillop, J. Behavioral economic analysis of stress effects on acute motivation for alcohol. J Exp Anal Behav. 2015. 103:77-86. doi:10.1002/jeab.114. | Intervention/Exposure
200. | Park, JL, Holcomb, RB, Raper, KC, Capps, O. A demand systems analysis of food commodities by US households segmented by income. American Journal of Agricultural Economics. 1996. 78:290-300. doi:10.2307/1243703. | Outcome
201. | Pearson, T, Russell, J, Campbell, MJ, Barker, ME. Do ‘food deserts’ influence fruit and vegetable consumption?--A cross-sectional study. Appetite. 2005. 45:195-7. doi:10.1016/j.appet.2005.04.003. | Outcome
202. | Pechey, R, Monsivais, P. Supermarket Choice, Shopping Behavior, Socioeconomic Status, and Food Purchases. Am J Prev Med. 2015. 49:868-77. doi:10.1016/j.amepre.2015.04.020. | Country
203. | Pechey, R, Monsivais, P, Ng, YL, Marteau, TM. Why don’t poor men eat fruit? Socioeconomic differences in motivations for fruit consumption. Appetite. 2015. 84:271-9. doi:10.1016/j.appet.2014.10.022. | Country
204. | Pechey, R, Monsivais, P. Socioeconomic inequalities in the healthiness of food choices: Exploring the contributions of food expenditures. Preventive medicine. 2016. 88:203-209. | Country
205. | Peñalvo, JL, Cudhea, F, Micha, R, Rehm, CD, Afshin, A, Whitsel, L, Wilde, P, Gaziano, T, Pearson-Stuttard, J, O’Flaherty, M, Capewell, S, Mozaffarian, D. The potential impact of food taxes and subsidies on cardiovascular disease and diabetes burden and disparities in the United States. BMC Med. 2017. 15:208. doi:10.1186/s12916-017-0971-9. | Outcome
206. | Peng, K, Kaza, N. Association between Neighborhood Food Access, Household Income, and Purchase of Snacks and Beverages in the United States. Int J Environ Res Public Health. 2020. 17:doi:10.3390/ijerph17207517. | Outcome
207. | Powell, LM. Fast food costs and adolescent body mass index: evidence from panel data. J Health Econ. 2009. 28:963-70. doi:10.1016/j.jhealeco.2009.06.009. | Outcome
208. | Powell, LM, Auld, MC, Chaloupka, FJ, O’Malley, PM, Johnston, LD. Access to fast food and food prices: relationship with fruit and vegetable consumption and overweight among adolescents. Adv Health Econ Health Serv Res. 2007. 17:23-48. | Outcome
209. | Powell, LM, Bao, Y. Food prices, access to food outlets and child weight. Econ Hum Biol. 2009. 7:64-72. doi:10.1016/j.ehb.2009.01.004. | Outcome
210. | Powell, LM, Han, E. The costs of food at home and away from home and consumption patterns among U.S. adolescents. J Adolesc Health. 2011. 48:20-6. doi:10.1016/j.jadohealth.2010.06.006. | Outcome
211. | Powell, LM, Han, E, Chaloupka, FJ. Economic Contextual Factors, Food Consumption, and Obesity among US Adolescents. Journal of Nutrition. 2010. 140:1175-1180. doi:10.3945/jn.109.111526. | Study Design
212. | Powell, LM, Jones, K, Duran, AC, Tarlov, E, Zenk, SN. The price of ultra-processed foods and beverages and adult body weight: Evidence from U.S. veterans. Econ Hum Biol. 2019. 34:39-48. doi:10.1016/j.ehb.2019.05.006. | Intervention/Exposure
213. | Powell, LM, Kumanyika, SK, Isgor, Z, Rimkus, L, Zenk, SN, Chaloupka, FJ. Price promotions for food and beverage products in a nationwide sample of food stores. Prev Med. 2016. 86:106-13. doi:10.1016/j.ypmed.2016.01.011. | Intervention/Exposure
214. | Powell, LM, Wada, R, Krauss, RC, Wang, Y. Ethnic disparities in adolescent body mass index in the United States: the role of parental socioeconomic status and economic contextual factors. Soc Sci Med. 2012. 75:469-76. doi:10.1016/j.socscimed.2012.03.019. | Outcome
215. | Powell, LM, Zhao, Z, Wang, Y. Food prices and fruit and vegetable consumption among young American adults. Health Place. 2009. 15:1064-70. doi:10.1016/j.healthplace.2009.05.002. | Outcome
216. | Powell, LM, Slater, S, Mirtcheva, D, Bao, Y, Chaloupka, FJ. Food store availability and neighborhood characteristics in the United States. Preventive medicine. 2007. 44:189-195. | Outcome
217. | Powell, LM Han, EEuna. Adult Obesity and the Price and Availability of Food in the United States. American Journal of Agricultural Economics. 2011. 93:378-384. doi:10.1093/ajae/aaq106. | Outcome
218. | Ramezani, CA, Rose, D, Murphy, S. AGGREGATION, FLEXIBLE FORMS, AND ESTIMATION OF FOOD-CONSUMPTION PARAMETERS. American Journal of Agricultural Economics. 1995. 77:525-532. doi:10.2307/1243221. | Intervention/Exposure
219. | Raper, KC, Wanzala, M Namakhoye, Nayga, RM. Food expenditures and household demographic composition in the US: a demand systems approach. Applied Economics. 2002. 34:981-992. doi:10.1080/00036840110061959. | Outcome
220. | Reed, J, Frazão, E, Itskowitz, R. How much do Americans pay for fruits and vegetables? 2004. | Intervention/Exposure
221. | Rehm, CD, Monsivais, P, Drewnowski, A. The quality and monetary value of diets consumed by adults in the United States. Am J Clin Nutr. 2011. 94:1333-9. doi:10.3945/ajcn.111.015560. | Outcome
222. | Rose, CM, Gupta, S, Buszkiewicz, J, Ko, LK, Mou, J, Cook, A, Moudon, AV, Aggarwal, A, Drewnowski, A. Small increments in diet cost can improve compliance with the Dietary Guidelines for Americans. Soc Sci Med. 2020. 266:113359. doi:10.1016/j.socscimed.2020.113359. | Outcome
223. | Rose, D. Access to healthy food: a key focus for research on domestic food insecurity. J Nutr. 2010. 140:1167-9. doi:10.3945/jn.109.113183. | Study Design
224. | Rummo, PE, Meyer, KA, Green Howard, A, Shikany, JM, Guilkey, DK, Gordon-Larsen, P. Fast food price, diet behavior, and cardiometabolic health: Differential associations by neighborhood SES and neighborhood fast food restaurant availability in the CARDIA study. Health Place. 2015. 35:128-35. doi:10.1016/j.healthplace.2015.06.010. | Outcome
225. | Sanjeevi, N, Freeland-Graves, JH. Association of Grocery Expenditure Relative to Thrifty Food Plan Cost with Diet Quality of Women Participating in the Supplemental Nutrition Assistance Program. J Acad Nutr Diet. 2018. 118:2315-2323. doi:10.1016/j.jand.2018.07.015. | Intervention/Exposure
226. | Semega, J, Kollar, M, Creamer, J, Mohan, A. Income and Poverty in the United States: 2018. 2020. 88. | Outcome
227. | Shannon, J. Beyond the supermarket solution: Linking food deserts, neighborhood context, and everyday mobility. Annals of the American Association of Geographers. 2016. 106:186-202. | Outcome
228. | Shaver, ER, Sadler, RC, Hill, AB, Bell, K, Ray, M, Choy-Shin, J, Lerner, J, Soldner, T, Jones, AD. The Flint Food Store Survey: combining spatial analysis with a modified Nutrition Environment Measures Survey in Stores (NEMS-S) to measure the community and consumer nutrition environments. Public Health Nutr. 2018. 21:1474-1485. doi:10.1017/s1368980017003950. | Outcome
229. | Shikany, JM, Carson, TL, Hardy, CM, Li, Y, Sterling, S, Hardy, S, Walker, CM, Baskin, ML. Assessment of the nutrition environment in rural counties in the Deep South. J Nutr Sci. 2018. 7:e27. doi:10.1017/jns.2018.18. | Comparator
230. | Singleton, CR, Fouché, S, Deshpande, R, Odoms-Young, A, Chatman, C, Spreen, C. Barriers to fruit and vegetable consumption among farmers’ market incentive programme users in Illinois, USA. Public Health Nutr. 2018. 21:1345-1349. doi:10.1017/s1368980018000101. | Comparator
231. | Smith, C, Butterfass, J, Richards, R. Environment influences food access and resulting shopping and dietary behaviors among homeless Minnesotans living in food deserts. Agriculture and Human Values. 2010. 27:141-161. doi:10.1007/s10460-009-9191-z. | Other factors
232. | Smith, Travis A, Huang, Chung L, Lin, Biing-Hwan. Does price or income affect organic choice? Analysis of US fresh produce users. 2009. | Outcome
233. | Spoden, AL, Buszkiewicz, JH, Drewnowski, A, Long, MC, Otten, JJ. Seattle’s minimum wage ordinance did not affect supermarket food prices by food processing category. Public Health Nutr. 2018. 21:1762-1770. doi:10.1017/s1368980017004037. | Intervention/Exposure
234. | Stallings, TL, Gazmararian, JA, Goodman, M, Kleinbaum, D. Agreement between the Perceived and Actual Fruit and Vegetable Nutrition Environments among Low-Income Urban Women. J Health Care Poor Underserved. 2015. 26:1304-18. doi:10.1353/hpu.2015.0109. | Intervention/Exposure
235. | Steenhuis, IH, Waterlander, WE, de Mul, A. Consumer food choices: the role of price and pricing strategies. Public Health Nutr. 2011. 14:2220-6. doi:10.1017/s1368980011001637. | Country
236. | Stegelin, F. Is Being Big Better? Shoppers Compare Food Merchandisers. 2016. 47:2. doi:10.22004/ag.econ.232317. | Comparator
237. | Steptoe, A, Pollard, TM, Wardle, J. Development of a measure of the motives underlying the selection of food: the food choice questionnaire. Appetite. 1995. 25:267-84. doi:10.1006/appe.1995.0061. | Country
238. | Stewart, H, Blisard, N. Who pays more for food? Journal of Agricultural Economics. 2008. 59:150-168. doi:10.1111/j.1477-9552.2007.00139.x. | Outcome
239. | Stewart, H, Blisard, N. The Thrifty Food Plan and low-income households in the United States: What food groups are being neglected? Food Policy. 2006. 31:469-482. doi:10.1016/j.foodpol.2005.12.002. | Outcome
240. | Stewart, H, Hyman, J, Frazão, E, Buzby, JC, Carlson, A. Can low-income Americans afford to satisfy MyPyramid fruit and vegetable guidelines? J Nutr Educ Behav. 2011. 43:173-9. doi:10.1016/j.jneb.2010.08.011. | Intervention/Exposure
241. | Sturm, R, Datar, A. Regional price differences and food consumption frequency among elementary school children. Public Health. 2011. 125:136-41. doi:10.1016/j.puhe.2010.11.016. | Outcome
242. | Sturm, R, Datar, A. Body mass index in elementary school children, metropolitan area food prices and food outlet density. Public Health. 2005. 119:1059-68. doi:10.1016/j.puhe.2005.05.007. | Intervention/Exposure
243. | Sullivan, CM, Pencak, JA, Freedman, DA, Huml, AM, León, JB, Nemcek, J, Theurer, J, Sehgal, AR. Comparison of the Availability and Cost of Foods Compatible With a Renal Diet Versus an Unrestricted Diet Using the Nutrition Environment Measures Survey. J Ren Nutr. 2017. 27:183-186. doi:10.1053/j.jrn.2016.12.008. | Intervention/Exposure
244. | Tach, L, Amorim, M. Constrained, Convenient, and Symbolic Consumption: Neighborhood Food Environments and Economic Coping Strategies among the Urban Poor. J Urban Health. 2015. 92:815-34. doi:10.1007/s11524-015-9984-x. | Intervention/Exposure
245. | Taylor, R, Villas-Boas, SB. FOOD STORE CHOICES OF POOR HOUSEHOLDS: A DISCRETE CHOICE ANALYSIS OF THE NATIONAL HOUSEHOLD FOOD ACQUISITION AND PURCHASE SURVEY (FOODAPS). American Journal of Agricultural Economics. 2016. 98:513-532. doi:10.1093/ajae/aaw009. | Outcome
246. | Townsend, MS, Aaron, GJ, Monsivais, P, Keim, NL, Drewnowski, A. Less-energy-dense diets of low-income women in California are associated with higher energy-adjusted diet costs. Am J Clin Nutr. 2009. 89:1220-6. doi:10.3945/ajcn.2008.26916. | Intervention/Exposure
247. | Trapl, ES, Pike, SN, Borawski, E, Flocke, SA, Freedman, DA, Walsh, CC, Schneider, C, Yoder, L. Food Melt in Consumer Food Environments in Low-income Urban Neighborhoods. Am J Health Behav. 2017. 41:710-718. doi:10.5993/ajhb.41.6.5. | Comparator
248. | Treno, AJ, Gruenewald, PJ, Wood, DS, Ponicki, WR. The price of alcohol: a consideration of contextual factors. Alcohol Clin Exp Res. 2006. 30:1734-42. doi:10.1111/j.1530-0277.2006.00207.x. | Outcome
249. | Tschirley, DL, Rose, D. Developing Cost Effective Methods for Estimating Household Income and Nutrient Intake Adequacy. 2000. 6. doi:10.22004/ag.econ.11330. | Country
250. | Valera, P, Gallin, J, Schuk, D, Davis, N. ‘‘Trying to Eat Healthy’’ A Photovoice Study About Women’s Access to Healthy Food in New York City. Affilia. 2009. 24:300-314. | Comparator
251. | Valluri, S, French, SA, Elbel, B, Oakes, JM, Rydell, SA, Harnack, LJ. Within- and Between-Household Variation in Food Expenditures Among Low-Income Households Using a Novel Simple Annotated Receipt Method. Front Nutr. 2020. 7:582999. doi:10.3389/fnut.2020.582999. | Intervention/Exposure
252. | Ver Ploeg, M, Rahko vs.ky, I. Recent Evidence on the Effects of Food Store Access on Food Choice and Diet Quality. 2016. 1. doi:10.22004/ag.econ.244274. | Outcome
253. | Vogel, C, Ntani, G, Inskip, H, Barker, M, Cummins, S, Cooper, C, Moon, G, Baird, J. Education and the Relationship Between Supermarket Environment and Diet. Am J Prev Med. 2016. 51:e27-e34. doi:10.1016/j.amepre.2016.02.030. | Country
254. | Volpe, R. WIC Foods Cost More in Smaller Stores. 2014. 1. doi:10.22004/ag.econ.210848. | Intervention/Exposure
255. | Wada, R, Han, EN, Powell, LM. Associations between soda prices and intake: Evidence from 24-h dietary recall data. Food Policy. 2015. 55:54-60. doi:10.1016/j.foodpol.2015.05.009. | Outcome
256. | Walker, RE, Fryer, CS, Butler, J, Keane, CR, Kriska, A, Burke, JG. Factors influencing food buying practices in residents of a low-income food desert and a low-income food oasis. Journal of Mixed Methods Research. 2011. 5:247-267. | Comparator
257. | Walker, TA, Lee, JS. Changes in key food purchasing practices of Supplemental Nutrition Assistance Program (SNAP)-eligible older adults following SNAP benefit receipt. Transl Behav Med. 2020. 10:1286-1296. doi:10.1093/tbm/ibaa029. | Comparator
258. | Waterlander, WE, de Haas, WE, van Amstel, I, Schuit, AJ, Twisk, JWR, Visser, M, Seidell, JC, Steenhuis, IHM. Energy density, energy costs and income–how are they related? Public health nutrition. 2010. 13:1599-1608. | Country
259. | Weatherspoon, D, Oehmke, J, Dembélé, A, Coleman, M, Satimanon, T, Weatherspoon, L. Price and Expenditure Elasticities for Fresh Fruits in an Urban Food Desert. Urban Studies (Sage Publications, Ltd.). 2013. 50:88-106. doi:10.1177/0042098012448555. | Intervention/Exposure
260. | Webber, CB, Sobal, J, Dollahite, JS. Shopping for fruits and vegetables. Food and retail qualities of importance to low-income households at the grocery store. Appetite. 2010. 54:297-303. doi:10.1016/j.appet.2009.11.015. | Comparator
261. | Weber, JA. Increasing food costs for consumers and food programs straining pocketbooks. J Am Diet Assoc. 2008. 108:615-7. doi:10.1016/j.jada.2008.02.010. | Study Design
262. | Wiig, K, Smith, C. The art of grocery shopping on a food stamp budget: factors influencing the food choices of low-income women as they try to make ends meet. Public Health Nutr. 2009. 12:1726-34. doi:10.1017/s1368980008004102. | Outcome
263. | Wilde, PE, Andrews, MS. The Food Stamp Program in an Era of Welfare Reform: Electronic Benefits and Changing Sources of Cash Income. Journal of Consumer Affairs. 2000. 34:31. doi:10.1111/j.1745-6606.2000.tb00082.x. | Outcome
264. | Winham, DM, Knoblauch, ST, Heer, MM, Thompson, SV, Der Ananian, C. African-American Views of Food Choices and Use of Traditional Foods. Am J Health Behav. 2020. 44:848-863. doi:10.5993/ajhb.44.6.9. | Outcome
265. | Winicki, J, Gundersen, C, Jolliffe, D. ISSUES IN FOOD ASSISTANCE - HOW DO FOOD ASSISTANCE PROGRAMS IMPROVE THE WELL-BEING OF LOW-INCOME FAMILIES? 2002. 4. doi:10.22004/ag.econ.262255. | Outcome
266. | Yen, ST, Lin, B-H, Smallwood, DM, Andrews, M. Demand for Nonalcoholic Beverages: The Case of Low-Income Households. Agribusiness. 2004. 20:309-321. doi:10.1002/agr.20015. | Outcome
267. | Young, CM, Batch, BC, Svetkey, LP. Effect of socioeconomic status on food availability and cost of the Dietary Approaches to Stop Hypertension (DASH) dietary pattern. J Clin Hypertens (Greenwich). 2008. 10:603-11. doi:10.1111/j.1751-7176.2008.08199.x. | Intervention/Exposure
268. | Zeballos, E, Sinclair, W. Average Share of Income Spent on Food in the United States Remained Relatively Steady From 2000 to 2019. 2020. 2020:doi:10.22004/ag.econ.307278. | Comparator
269. | Zenk, SN, Schulz, AJ, Israel, BA, James, SA, Bao, S, Wilson, ML. Fruit and vegetable access differs by community racial composition and socioeconomic position in Detroit, Michigan. Ethn Dis. 2006. 16:275-280. | Intervention/Exposure
270. | Zenk, SN, Schulz, AJ, Lachance, LL, Mentz, G, Kannan, S, Ridella, W, Galea, S. Multilevel correlates of satisfaction with neighborhood availability of fresh fruits and vegetables. Ann Behav Med. 2009. 38:48-59. doi:10.1007/s12160-009-9106-7. | Outcome
271. | Zhang, G, You, W, Carlson, A, Lin, B-H. The Impact of Regional Food Cost Differences on the TFP Recommendations. 2010. 2. doi:10.22004/ag.econ.61643. | Comparator
272. | Zhang, Q, Chen, Z, Diawara, N, Wang, Y. Prices of unhealthy foods, Food Stamp Program participation, and body weight status among U.S. low-income women. J Fam Econ Issues. 2011. 32:245-256. doi:10.1007/s10834-010-9228-x. | Comparator
273. | Zhang, Q, Jones, S, Ruhm, CJ, Andrews, M. Higher food prices may threaten food security status among American low-income households with children. J Nutr. 2013. 143:1659-65. doi:10.3945/jn.112.170506. | Outcome
274. | Zhao, AW, McGowan, CC, Zenk, SN, Kershaw, KN. Associations of the consumer food environment with eating behaviours and BMI. Public Health Nutr. 2020. 23:3197-3203. doi:10.1017/s1368980020002633. | Intervention/Exposure