# Appendix 1-a Literature search strategy for the rapid review on income and food prices

Database: PubMed

Vendor: National Library of Medicine

Date of Search: February 8, 2021

Limits Used: Filters: Language English; Publication Dates 1995 - 2021

Total = 4,265

Search # | Concept | Search String | N
#1 | Food/Beverages | “Food and Beverages”[Mesh] OR food*[tiab] OR vegetable*[tiab] OR fruit*[tiab] OR meat*[tiab] OR seafood*[tiab] OR poultry[tiab] OR beans[tiab] OR rice[tiab] OR legumes[tiab] OR cereal*[tiab] OR grain*[tiab] OR dairy[tiab] OR eggs[tiab] OR beverage*[tiab] OR milk[tiab] OR “Diet, Healthy”[Mesh] OR “healthy diet*”[tiab] OR “unhealthy diet*”[tiab] | 1,376,771
#2 | Price/Cost | “Costs and Cost Analysis”[Mesh] OR cost*[tiab] OR price*[tiab] OR affordab*[tiab] OR expense*[tiab] OR expenditure*[tiab] OR budget*[tiab] OR purchas*[tiab] OR cash[tiab] OR money[tiab] OR monetary[tiab] OR monies[tiab] | 918,203
| Income/social economic factors | “Socioeconomic Factors”[Mesh] OR socioeconomic*[tiab] OR socio-economic*[tiab] OR “social factor*”[tiab] OR “social condition*”[tiab] OR poverty[tiab] OR “Residence Characteristics”[Mesh] OR “Vulnerable Populations”[Mesh] OR “vulnerable population*”[tiab] OR “underserved population*”[tiab] OR “disadvantaged population*”[tiab] OR “Income”[Mesh] OR income*[tiab] OR “Race Factors”[Mesh] OR “race factor*”[tiab] OR “Ethnic Groups”[Mesh] OR “ethnic group*”[tiab] OR “ethnic population*”[tiab] OR “Cross-Cultural Comparison”[Mesh] OR “cross-cultural”[tiab] OR transcultural[tiab] OR “Cultural Characteristics”[Mesh] OR “cultural characteristic*”[tiab] OR “Cultural Diversity”[Mesh] OR “culturally diverse”[tiab] OR “Food Supply”[Mesh] OR “food desert*”[tiab] OR “food insecurit*”[tiab] OR “food environment*”[tiab] OR “food access”[tiab] OR “corner store*”[tiab] OR bodega*[tiab] OR “food cooperative*”[tiab] OR “food store*”[tiab] OR “food market*”[tiab] OR grocer*[tiab] OR supermarket*[tiab] OR “convenient store*”[tiab] OR “food outlet*”[tiab] OR “farmers market*”[tiab] | 873,818
#3 | | #1 AND #2 AND #3 | 11,345
#4 | Non-United States | #1 AND #2 AND #3 NOT (“Developing Countries”[Mesh] OR “developing countr*” OR “Under Developed Nation*” OR “low income countr*” OR “middle income countr*”OR “low-middle-income countr*” OR LMIC[tiab] OR “Europe”[Mesh] OR “Australia”[Mesh] OR “Asia”[Mesh] OR “Africa”[Mesh] OR “Mexico”[Mesh] OR “Islands”[Mesh] OR “Central America”[Mesh] OR “Latin America”[Mesh] OR “South America”[Mesh]) | 5,916
#4 | Publication Excludes | NOT (letter[ptyp] OR editorial[ptyp] OR comment[ptyp] OR news[ptyp] OR “Congress”[Publication Type] OR “Consensus Development Conference”[Publication Type] OR editorial[tiab] OR commentary[tiab] OR “conference abstract*”[tiab] OR “systematic review*”[ti] OR “meta-analysis”[ptyp] OR “meta-analysis”[ti] OR “meta-analyses”[ti] OR “Review”[Publication Type] OR “Systematic Review”[Publication Type] OR “conference proceeding*”[tiab] OR “retracted publication”[ptyp] OR “retraction of publication”[ptyp] OR “retraction of publication”[tiab] OR “retraction notice”[ti] OR “retracted publication”[tiab] OR “Published Erratum”[Publication Type] OR corrigenda[tiab] OR corrigendum[tiab] OR errata[tiab] OR erratum[tiab] OR protocol[ti] OR protocols[ti] OR “case report”[ti] OR “case series”[ti] OR “Case Reports” [Publication Type]) | 4,766
#5 | Animal Excludes | NOT (“Animals”[Mesh] NOT (“Animals”[Mesh] AND “Humans”[Mesh])) | 4,570
#6 | Limits: Language/Dates | Filters: English, from 1995 - 2021 | 4,265

Database: Cochrane Central Register of Controlled Trials (CENTRAL)

Vendor: John Wiley & Sons, Inc.

Date of Search: February 9, 2021

Limits Used: Filters: Trials; Publication Dates 1995 - 2021

Total = 847

Search # | Concept | Search String | N
#1 | Food/Beverages | [mh “Food and Beverages”] OR food* OR vegetable* OR fruit* OR meat* OR seafood* OR poultry OR beans OR rice OR legumes OR cereal* OR grain* OR dairy OR eggs OR beverage* OR milk OR [mh “Diet, Healthy”] OR “healthy diet*” OR “unhealthy diet*” | 96,092
#2 | Price/Cost | [mh “Costs and Cost Analysis”] OR cost* OR price* OR affordab* OR expense* OR expenditure* OR budget* OR purchas* OR cash OR money OR monetary OR monies | 99,584
#3 | Income/social economic factors | [mh “Socioeconomic Factors”] OR socioeconomic* OR socio-economic* OR “social factor*” OR “social condition*” OR poverty OR [mh “Residence Characteristics”] OR [mh “Vulnerable Populations”] OR “vulnerable population*” OR “underserved population*” OR “disadvantaged population*” OR [mh “Income”] OR income* OR [mh “Race Factors”] OR “race factor*” OR [mh “Ethnic Groups”] OR “ethnic group*” OR “ethnic population*” OR [mh “Cross-Cultural Comparison”] OR “cross-cultural” OR transcultural OR [mh “Cultural Characteristics”] OR “cultural characteristic*” OR [mh “Cultural Diversity”] OR “culturally diverse” OR [mh “Food Supply”] OR “food desert*” OR “food insecurit*” OR “food environment*” OR “food access” OR “corner store*” OR bodega* OR “food cooperative*” OR “food store*” OR “food market*” OR grocer* OR supermarket* OR “convenient store*” OR “food outlet*” OR “farmers market*” | 32,995
#4 | | #1 AND #2 AND #3 | 1,879
#5 | Non-United States | [mh “Developing Countries”] OR “developing countr*” OR “under developed nation*” OR “low income countr*” OR “middle income countr*” OR “low-middle-income countr*” OR LMIC OR [mh “Europe”] OR [mh “Australia”] OR [mh “Asia”] OR [mh “Africa”] OR [mh “Mexico”] OR [mh “Islands”] OR [mh “Central America”] OR [mh “Latin America”] OR [mh “South America”] | 5,916
#6 | | #4 NOT #5” with Publication Year from 1995 to 2021, in Trials (Word variations have been searched) | 847

Database: Business Source Premier

Vendor: EBSCO

Date of Search: February 9, 2021

Limits Used: Filters: Language English, Peer Reviewed, Academic Journal; Publication, Geographic United States, Dates 1995 - 2021

Total = 471

Search # | Concept | Search String | N
#S1 | Food/Beverages | (DE “BEVERAGE consumption”) OR (DE “FOOD consumption forecasting”) OR (DE “FOOD consumption statistics”) OR food* OR vegetable* OR fruit* OR meat* OR seafood* OR poultry OR beans OR rice OR legumes OR cereal* OR grain* OR dairy OR eggs OR beverage* OR milk OR “healthy diet*” OR “unhealthy diet*”; Limiters - Scholarly (Peer Reviewed) Journals; Published Date: 19950101-20211231; Publication Type: Academic Journal; Document Type: Article | 115,0411
#S2 | Price/Cost | (DE “FOOD prices”) OR cost* OR price* OR affordab* OR expense* OR expenditure* OR budget* OR purchas* OR cash OR money OR monetary OR monies; Limiters - Scholarly (Peer Reviewed) Journals; Published Date: 19950101-20211231; Publication Type: Academic Journal; Document Type: Article | 526,897
#S3 | Income/social economic factors | (DE “SOCIOECONOMIC factors”) OR socioeconomic* OR socio-economic* OR “social factor*” OR “social condition*” OR (DE “POVERTY”) OR poverty OR “vulnerable population*” OR “underserved population*” OR “disadvantaged population*” OR (DE “INCOME”) OR income* OR “race factor*” OR (DE “ECONOMIC conditions of ethnic groups”) OR “ethnic group*” OR “ethnic population*” OR “cross-cultural” OR transcultural OR “cultural characteristic*” OR “culturally diverse” OR (DE “FOOD supply”) OR “food desert*” OR “food insecurit*” OR “food environment*” OR “food access” OR “corner store*” OR bodega* OR “food cooperative*” OR “food store*” OR “food market*” OR grocer* OR supermarket* OR “convenient store*” OR “food outlet*” OR “farmers market*”; Limiters - Scholarly (Peer Reviewed) Journals; Published Date: 19950101-20211231; Publication Type: Academic Journal; Document Type: Article | 200,523
#S3 | | S1 AND S2 AND S3 | 6,977
#S4 | Non-United States | S1 AND S2 AND S3; Limiters - Scholarly (Peer Reviewed) Journals; Published Date: 19950101-20211231; Publication Type: Academic Journal; Document Type: Article; Geographic: - united states | 471

Database: Web of Science: Core Collection

Vendor: Clarivate Analytics

Date of Search: February 9, 2021

Limits Used: Filters: Language English; Publication Dates 1995 - 2021

Total = 4,040

Search # | Concept | Search String | N
#1 | Food & Beverages | (TS=(food* OR vegetable* OR fruit* OR meat* OR seafood* OR poultry OR beans OR rice OR legumes OR cereal* OR grain* OR dairy OR eggs OR beverage* OR milk OR “healthy diet*” OR “unhealthy diet*”) ) | 2,246,131
#2 | Price/Cost | (TS=(cost* OR price* OR affordab* OR expense* OR expenditure* OR budget* OR purchas* OR cash OR money OR monetary OR monies ) ) | 1,902,030
#3 | Income/social economic factors | (TS=(socioeconomic* OR socio-economic* OR “social factor*” OR “social condition*” OR poverty OR “residence characteristics” OR “vulnerable population*” OR “underserved population*” OR “disadvantaged population*” OR income* OR “race factor*” OR “ethnic group*” OR “ethnic population*” OR “cross-cultural” OR transcultural OR “cultural characteristic*” OR “culturally diverse” OR “food desert*” OR “food insecurit*” OR “food environment*” OR “food access” OR “corner store*” OR bodega* OR “food cooperative*” OR “food store*” OR “food market*” OR grocer* OR supermarket* OR “convenient store*” OR “food outlet*” OR “farmers market*”) | 562,183
#4 | | #1 AND #2 AND #3 | 17,069
#5 | Non-United States | CU=(“developing countr*” OR “under developed nation*” OR “low income countr*” OR “middle income countr*” OR “low-middle income countr*” OR LMIC; OR Europe OR Australia OR Asia OR Africa OR Mexico OR Islands OR “Central America” OR “Latin America” OR “South America”) | 2,281,865
#6 | | #4 NOT #5 | 15,059
#7 | Publication Excludes | TS=(editorial OR commentary OR “conference abstract*” OR “conference proceeding*”[tiab] OR “retraction of publication” OR “retracted publication” OR corrigenda[tiab] OR corrigendum[tiab] OR errata OR erratum OR “case reports” ) OR TI=(“systematic review*” OR “meta-analysis”; OR “meta analyses” OR protocol OR protocols; OR “retraction notice” OR “case report” OR; “case series”) | 731,825
#8 | Language/Dates | #6 NOT #7; AND LANGUAGE: (English) AND DOCUMENT TYPES: (Article) Refined by: COUNTRIES/REGIONS: (USA); Indexes=SCI-EXPANDED, SSCI Timespan=1995-2021 | 4040

## Grey literature Search

### Database: Google Scholar

(Food AND beverages OR “food basket” OR groceries) (Price OR cost OR expenditure OR budget OR money OR “exact price index”) AND (Income OR Poverty OR socioeconomic OR neighborhood OR city OR county)

Limits:

Date Searched: 4/26/2021

Results: 130, limited to 13 pages

### Database: Google

site:.gov pdf AND (Food AND beverages OR “food basket” OR groceries) (Price OR cost OR expenditure OR budget OR money OR “exact price index”) AND (Income OR Poverty OR socioeconomic OR neighborhood OR city OR county)

Limits:

Date Searched: 4/26/2021

Results: 30, limited to 3 pages

### Database: AgEcon

#### Search A

Any of the words: food beverage basket grocer*

AND

Any of the words: cost price

AND

Any of the words: income

Limits:

Date Searched: 4/27/2021

Results: 100, limited to 10 pages

#### Search B

Any of the words: food beverage basket grocer*

AND

Any of the words: cost price

AND

Any of the words: neighborhood

Limits:

Date Searched: 4/27/2021

Results: 40, limited to 4 pages

#### Search C

Any of the words: food beverage basket grocer*

AND

Any of the words: cost price

AND

Any of the words: poverty

Limits:

Date Searched: 4/27/2021

Results: 110, limited to 11 pages

#### Search D

Any of the words: food beverage basket grocer*

AND

Any of the words: cost price

AND

Any of the words: socioeconomic

Limits:

Date Searched: 4/27/2021

Results: 60, limited to 6 pages