# Appendix 5-b Excluded articles for the evidence scan on factors that influence the purchase and/or consumption of convenience foods

The following table lists the articles excluded after full-text screening for this evidence scan question. At least 1 reason for exclusion is provided for each article, though this may not reflect all possible reasons. Information about articles excluded after title and abstract screening is available upon request.

| Citation | Reason for exclusion
1. | . Are canned fruits and vegetables a healthy alternative to fresh produce? The Johns Hopkins medical letter health after 50. 2013. 25:7. | Outcome
2. | . Convenience food and drink sector. Nutrition & Food Science. 2010. 40:173-178. doi:10.1108/nfs.2010.01740dab.022. | Country
3. | . FASTLANE CONVENIENCE. 2021. | Outcome
4. | . Fresh or frozen produce? The health benefit is all in the mix. Relying on a mix of fresh and frozen can help you get your five-to-nine daily servings of fruits and vegetables. Harvard men’s health watch. 2014. 18:6. | Outcome
5. | . From Other Blogs: National Immunization Awareness Month, convenience foods, disaster recovery & more. Live Healthy SC. 2018. | Study design
6. | . International chefs’ circle promotes quality ready meals. Food Australia. 2008. 60:94. | Country; Publication status
7. | . ready-to-eat food samples: Topics by Science.gov. 2021. | Other
8. | Ailawadi, K, Ma, Y, Grewal, D. The club store effect: Impact of shopping in warehouse club stores on consumers’ packaged food purchases. Journal of Marketing Research. 2018. 55:193-207. doi:10.1509/jmr.16.0235. | Outcome
9. | Albuquerque, P, Bronnenberg, BJ. Estimating demand heterogeneity using aggregated data: An application to the frozen pizza category. Marketing Science. 2009. 28:356-372. doi:10.1287/mksc.1080.0403. | Intervention/Exposure; Data date range
10. | Alpaugh, M, Pope, L, Trubek, A, Skelly, J, Harvey, J. Cooking as a health behavior: Examining the role of cooking classes in a weight loss intervention. Nutrients. 2020. 12:1-13. doi:10.3390/nu12123669. | Outcome
11. | Andrews, SandraL, O’Reilly, Donna . Storing Designer And Convenience Foods. Extension Bulletin E-2297 Cooperative Extension Service. 1991. 6. | Outcome
12. | Anesbury, Zachary William, Talbot, Danielle, Day, Chanel Andrea, Bogomolov, Tim, Bogomolova, Svetlana. The fallacy of the heavy buyer: Exploring purchasing frequencies of fresh fruit and vegetable categories. Journal of Retailing & Consumer Services. 2020. 53:N.PAG-N.PAG. doi:10.1016/j.jretconser.2019.101976. | Intervention/Exposure
13. | Anselmsson, Johan, Bondesson, Niklas Vestman, Johansson, Ulf. Brand image and customers’ willingness to pay a price premium for food brands. Journal of Product & Brand Management. 2014. 23:90-102. doi:10.1108/JPBM-10-2013-0414. | Country
14. | Arentz, L. Kidney-Friendly Frozen Meals Update: Quick and Convenient Options for Chronic Kidney Disease Patients. Journal of Renal Nutrition. 2016. 26:e15-e17. doi:10.1053/j.jrn.2016.02.004. | Outcome
15. | Aviles, M Victoria, Naef, Elisa Fernanda, Abalos, Rosa Ana, Lound, Liliana H, Olivera, Daniela F, García-Segovia, Purificación. Effect of familiarity of ready-to-eat animal-based meals on consumers’ perception and consumption motivation. International Journal of Gastronomy and Food Science. 2020. 21:100225. | Country
16. | Ayala, GX, Baquero, B, Laraia, BA, Ji, M, Linnan, L. Efficacy of a store-based environmental change intervention compared with a delayed treatment control condition on store customers’ intake of fruits and vegetables. Public Health Nutrition. 2013. 16:1953-1960. doi:10.1017/S1368980013000955. | Outcome
17. | Baker, SL, McCabe, SD, Swithers, SE, Payne, CR, Kranz, S. Do healthy, child-friendly fruit and vegetable snacks appeal to consumers? A field study exploring adults’ perceptions and purchase intentions. Food Quality and Preference. 2015. 39:202-208. doi:10.1016/j.foodqual.2014.07.013. | Outcome
18. | Balzan, S, Fasolato, L, Cardazzo, B, Berti, G, Novelli, E. Cold Chain and Consumers’ Practices: Exploratory Results of Focus Group Interviews. Ital J Food Saf. 2014. 3:4516. doi:10.4081/ijfs.2014.4516. | Country
19. | Barska, Anetta. Millennial consumers in the convenience food market. Konsumenci generacji Y na rynku żywności wygodnej.. 2018. 22:251-264. doi:10.2478/manment-2018-0018. | Country
20. | Baumhofer, NK, Panapasa, SV, Francis Cook, E, Roberto, CA, Williams, DR. Sociodemographic factors influencing island foods consumption in the Pacific Islander Health Study. Ethnicity and Health. 2020. 25:305-321. doi:10.1080/13557858.2017.1418300. | Outcome
21. | Berge, JM, Tate, A, Trofholz, A, Loth, K, Miner, M, Crow, S, Neumark-Sztainer, D. Examining variability in parent feeding practices within a low-income, racially/ethnically diverse, and immigrant population using ecological momentary assessment. Appetite. 2018. 127:110-118. doi:10.1016/j.appet.2018.04.006. | Outcome
22. | Binkley, JK, Liu, Y. Food at Home and away from Home: Commodity Composition, Nutrition Differences, and Differences in Consumers. Agricultural and Resource Economics Review. 2019. 48:221-252. doi:10.1017/age.2019.1. | Intervention/Exposure
23. | Bird Jernigan, Valarie Blue, Salvatore, AliciaL, Williams, Mary, Wetherill, Marianna, Taniguchi, Tori, Jacob, Tvli, Cannady, Tamela, Grammar, Mandy, Standridge, Joy, Fox, Jill, Tingle Owens, JoAnna, Spiegel, Jennifer, Love, Charlotte, Teague, Travis, Noonan, Carolyn. A Healthy Retail Intervention in Native American Convenience Stores: The THRIVE Community-Based Participatory Research Study. American Journal of Public Health. 2019. 109:132-139. doi:10.2105/AJPH.2018.304749. | Outcome
24. | Bishop, L, Goeddeke-Merickel, CM. Kidney-Friendly Frozen Meal Tips and Suggestions “In A Pinch”. Journal of Renal Nutrition. 2012. 22:e43-e45. doi:10.1053/j.jrn.2012.06.002. | Outcome; Study design
25. | Bodor, JN, Hutchinson, PL, Rose, D. Car ownership and the association between fruit and vegetable availability and diet. Preventive Medicine. 2013. 57:903-905. doi:10.1016/j.ypmed.2013.10.003. | Outcome
26. | Bosworth, RC, Bailey, D, Curtis, KR. Consumer Willingness to Pay for Local Designations: Brand Effects and Heterogeneity at the Retail Level. Journal of Food Products Marketing. 2015. 21:274-292. doi:10.1080/10454446.2013.843488. | Outcome
27. | Bower, Patrick. Forecasting New Products in Consumer Goods. Journal of Business Forecasting. 2012. 31:4-30. | Outcome
28. | Brauchla, M, Fulgoni, VL. Cost-effective Options for Increasing Consumption of Under-consumed Food Groups & Nutrients in the United States. Public Health Nutrition. 2021. doi:10.1017/S1368980021000537. | Outcome
29. | Briefel, RR, Chojnacki, GJ, Gabor, V, Forrestal, SG, Kleinman, R, Cabili, C, Gleason, PM. A Cluster Randomized Controlled Trial of a Home-Delivered Food Box on Food Security in Chickasaw Nation. Journal of the Academy of Nutrition and Dietetics. 2021. 121:S46-S58. doi:10.1016/j.jand.2020.07.021. | Outcome
30. | Briefel, RR, Collins, AM, Wolf, A, Gordon, AR, Cabili, CL, Klerman, JA. Nutrition impacts in a randomized trial of summer food benefits to prevent childhood hunger in U.S. schoolchildren. Journal of Hunger and Environmental Nutrition. 2018. 13:304-321. doi:10.1080/19320248.2017.1393366. | Outcome
31. | Briefel, RR, Wilson, A, Gleason, PM. Consumption of Low-Nutrient, Energy-Dense Foods and Beverages at School, Home, and Other Locations among School Lunch Participants and Nonparticipants. Journal of the American Dietetic Association. 2009. 109:S79-S90. doi:10.1016/j.jada.2008.10.064. | Data date range
32. | Burani, J. Home cooking. Eat healthy, save money!. Diabetes self-management. 2010. 27: | Publication status
33. | Camire, ME, Savoie, K, Perry, J, Calder, B. Preliminary assessment of maine consumers’ educational preferences for fermenting foods at home. Food Protection Trends. 2019. 39:116-126. | Outcome
34. | Canuto, R, Garcez, A, Spritzer, PM, Olinto, MTA. Associations of perceived stress and salivary cortisol with the snack and fast-food dietary pattern in women shift workers. Stress. 2021. 1-9. doi:10.1080/10253890.2021.1919615. | Country
35. | Caspi, CE, Lenk, K, Pelletier, JE, Barnes, TL, Harnack, L, Erickson, DJ, Laska, MN. Association between store food environment and customer purchases in small grocery stores, gas-marts, pharmacies and dollar stores. International Journal of Behavioral Nutrition and Physical Activity. 2017. 14:doi:10.1186/s12966-017-0531-x. | Outcome
36. | Chae, Mi-Jin, Bae, Hyun-Joo. A survey on preference and satisfaction of the customers purchasing ready-to-eat foods. Korean Journal of Food and Cookery Science. 2008. 24:788-800. | Country; Data date range
37. | Chen, Danhong, Jaenicke, EdwardC. Composition of Food-at-Home Expenditures and Childhood Obesity. 2017. doi:10.22004/ag.econ.258343. | Publication status
38. | Chen, Y, Lin, BH, Mancino, L, Ploeg, MV, Zhen, C. Nutritional quality of retail food purchases is not associated with participation in the Supplemental Nutrition Assistance Program for nutrition-oriented households. PLoS ONE. 2020. 15:doi:10.1371/journal.pone.0240263. | Outcome
39. | Chonpracha, P, Ardoin, R, Gao, Y, Waimaleongoraek, P, Tuuri, G, Prinyawiwatkul, W. Effects of intrinsic and extrinsic visual cues on consumer emotion and purchase intent: A case of ready-to-eat salad. Foods. 2020. 9:doi:10.3390/foods9040396. | Outcome
40. | Chu, J, Chintagunta, P, Cebollada, J. A comparison of within-household price sensitivity across online and offline channels. Marketing Science. 2008. 27:283-299. doi:10.1287/mksc.1070.0288. | Country
41. | Cioffi, CE, Levitsky, DA, Pacanowski, CR, Bertz, F. A nudge in a healthy direction. The effect of nutrition labels on food purchasing behaviors in university dining facilities. Appetite. 2015. 92:7-14. doi:10.1016/j.appet.2015.04.053. | Outcome; Other
42. | Cleary, R, Bonanno, A, Ghazaryan, A, Bellows, L, McCloskey, M. School meals and quality of household food acquisitions. Applied Economic Perspectives and Policy. 2021. doi:10.1002/aepp.13130. | Outcome
43. | Coffman, MA, Camire, ME. Perceived Barriers to Increased Whole Grain Consumption by Older Adults in Long-Term Care. Journal of Nutrition in Gerontology and Geriatrics. 2017. 36:178-188. doi:10.1080/21551197.2017.1385564. | Outcome
44. | Colasanti, KJA, Matts, C, Hamm, MW. Results from the 2009 Michigan Farm to School Survey: Participation Grows from 2004. Journal of Nutrition Education and Behavior. 2012. 44:343-349. doi:10.1016/j.jneb.2011.12.003. | Outcome
45. | Combs, Susan. Local Sales Tax and Use Bulletin: Ready-To-Eat Food . 2007. | Data date range
46. | Conrad, Z, Chui, K, Jahns, L, Peters, CJ, Griffin, TS. Characterizing trends in fruit and vegetable intake in the USA by self-report and by supply-And-disappearance data: 2001-2014. Public Health Nutrition. 2017. 20:3045-3050. doi:10.1017/S1368980017002385. | Intervention/Exposure
47. | Contini, Caterina, Romano, Caterina, Scozzafava, Gabriele, Casini, Leonardo. Food habits and the increase in ready-to-eat and easy-to-prepare products. Food hygiene and toxicology in ready-to-eat foods. 2016. 3-14. | Study design
48. | Cook, R. Fresh-cut/value-added produce marketing trends. UC Davis freshcut products workshop: maintaining quality and safety. 2016. | Study design
49. | Cornwell, TB, Setten, E, Paik, SHW, Pappu, R. Parents, Products, and the Development of Preferences: Child Palate and Food Choice in an Obesogenic Environment. Journal of Public Policy and Marketing. 2020. doi:10.1177/0743915620939581. | Outcome
50. | Dallinger, I, Magnini, VP. Chefs’ perceptions of using convenience food products versus scratch cooking. Journal of Foodservice Business Research. 2017. 20:34-49. doi:10.1080/15378020.2016.1192892. | Outcome
51. | Dannefer, R, Bryan, E, Osborne, A, Sacks, R. Evaluation of the Farmers’ Markets for Kids programme. Public Health Nutrition. 2016. 19:3397-3405. doi:10.1017/S1368980016001725. | Outcome
52. | Davis, GC, You, W, Yang, Y. Are SNAP benefits adequate? A geographical and food expenditure decomposition. Food Policy. 2020. 95:doi:10.1016/j.foodpol.2020.101917. | Outcome
53. | Dettmann, RL, Dimitri, C. Who’s buying organic vegetables? Demographic characteristics of U.S. consumers. Journal of Food Products Marketing. 2010. 16:79-91. doi:10.1080/10454440903415709. | Data date range
54. | DeWeese, RS, Ohri-Vachaspati, P. Cost of Children’s Healthy vs. Unhealthy Snacks Does Not Differ at Convenience Stores. Journal of Nutrition Education and Behavior. 2017. 49:241-243.e1. doi:10.1016/j.jneb.2016.11.006. | Outcome
55. | Dhir, Bhavya, Singla, Neerja. Consumption Pattern and Health Implications of Convenience Foods: A Practical Review. Current Journal of Applied Science and Technology. 2019. 1-9. | Country
56. | Di Noia, J, Monica, D, Cullen, KW, Pérez-Escamilla, R, Gray, HL, Sikorskii, A. Differences in fruit and vegetable intake by race/ethnicity and by hispanic origin and nativity among women in the special supplemental nutrition program for women, infants, and children, 2015. Preventing Chronic Disease. 2016. 13:doi:10.5888/pcd13.160130. | Outcome
57. | Didinger, C, Thompson, H. Motivating pulse-centric eating patterns to benefit human and environmental well-being. Nutrients. 2020. 12:1-12. doi:10.3390/nu12113500. | Study design
58. | Disantis, KI, Grier, SA, Oakes, JM, Kumanyika, SK. Food prices and food shopping decisions of black women. Appetite. 2014. 77:104-112. doi:10.1016/j.appet.2014.02.016. | Outcome
59. | Dong, Diansheng, Kaiser, HarryM. Investigating household food interpurchase behavior through market segmentation. Agribusiness. 2010. 26:389-404. doi:10.1002/agr.20230. | Data date range
60. | Espinoza-Orias, Namy, Azapagic, Adisa. Understanding the impact on climate change of convenience food: Carbon footprint of sandwiches. Sustainable Production and Consumption. 2018. 15:1-15. | Outcome
61. | Findholt, NE, Izumi, BT, Nguyen, T, Pickus, H, Chen, Z. Availability of healthy snack foods and beverages in stores near high-income urban, low-income urban, and rural elementary and middle schools in Oregon. Childhood Obesity. 2014. 10:342-348. doi:10.1089/chi.2014.0020. | Outcome
62. | Gabrielli, Veronica, Cavazza, Nicoletta. The influence of in-store product holders on orientation towards the product and on purchase intention. International Review of Retail, Distribution & Consumer Research. 2014. 24:311-327. doi:10.1080/09593969.2013.862507. | Country
63. | Gajda, R, Bronkowska, M. Dietary patterns of health sciences students in regarding to physical activity levels and somatic indicators of nutritional status. Rocz Panstw Zakl Hig. 2020. 71:271-278. doi:10.32394/rpzh.2020.0124. | Country
64. | Ghosh Roy, P, Jones, KK, Martyn-Nemeth, P, Zenk, SN. Contextual correlates of energy-dense snack food and sweetened beverage intake across the day in African American women: An application of ecological momentary assessment. Appetite. 2019. 132:73-81. doi:10.1016/j.appet.2018.09.018. | Other
65. | Graham, DJ, Mohr, GS. When zero is greater than one: Consumer misinterpretations of nutrition labels. Health Psychology. 2014. 33:1579-1587. doi:10.1037/hea0000080. | Intervention/Exposure; Outcome
66. | Guan, X, Atlas, SA, Vadiveloo, M. Targeted retail coupons influence category-level food purchases over 2-years 11 Medical and Health Sciences 1117 Public Health and Health Services. International Journal of Behavioral Nutrition and Physical Activity. 2018. 15:doi:10.1186/s12966-018-0744-7. | Data date range
67. | Gumirakiza, JD, Curtis, KR, Bosworth, R. Who attends farmers’ markets and why? Understanding consumers and their motivations. International Food and Agribusiness Management Review. 2014. 17:65-82. | Outcome
68. | Guthrie, J, Mancino, L, Lin, CTJ. Nudging consumers toward better food choices: Policy approaches to changing food consumption behaviors. Psychology and Marketing. 2015. 32:501-511. doi:10.1002/mar.20795. | Study design
69. | Guthrie, Joanne , Lin, Biing-Hwan . Both At Home and Away, Americans Are Choosing More Lower Fat Foods Than They Did 35 Years Ago. 2018. October 2018:doi:10.22004/ag.econ.302659. | Outcome
70. | Ha, EJ, Caine-Bish, N. Effect of Nutrition Intervention Using a General Nutrition Course for Promoting Fruit and Vegetable Consumption among College Students. Journal of Nutrition Education and Behavior. 2009. 41:103-109. doi:10.1016/j.jneb.2008.07.001. | Data date range
71. | Haire, C, Raynor, HA. Weight status moderates the relationship between package size and food Intake. Journal of the Academy of Nutrition and Dietetics. 2014. 114:1251-1256. doi:10.1016/j.jand.2013.12.022. | Outcome
72. | Henderson, Steven . September, 20171 Comparing Global questions and answers to results from detailed specific questions: Data on Food Expenditures from the Consumer Expenditure Survey, 1998 - 2016. 2017. 5. | Outcome
73. | Hillier, A, McLaughlin, J, Cannuscio, CC, Chilton, M, Krasny, S, Karpyn, A. The Impact of WIC Food Package Changes on Access to Healthful Food in 2 Low-Income Urban Neighborhoods. Journal of Nutrition Education and Behavior. 2012. 44:210-216. doi:10.1016/j.jneb.2011.08.004. | Outcome
74. | Hirekenchanagoudar, Renuka. Consumer behaviour towards ready-to-eat food products. 2008. | Country
75. | Holloman, EL, Newman, MC. A community-based assessment of seafood consumption along the lower James River, Virginia, USA: Potential sources of dietary mercury exposure. Environmental Research. 2010. 110:213-219. doi:10.1016/j.envres.2010.01.002. | Intervention/Exposure
76. | Holzmeister, LA. Supermarket smarts. Fresh, frozen, and canned poultry. Diabetes self-management. 2008. 25:73, 75, 77-78, 80-81, 84-85. | Publication status
77. | Holzmeister, LA. Vegetarian frozen entrées. Diabetes self-management. 2010. 27:52, 54, 56-60. | Publication status
78. | Hoseini Siahdashti, Seyed Jaber. Investigating the Role of Food Packaging in Terms of Design and Color in Consumer Purchasing Behavior. International Journal of Management, Accounting & Economics. 2019. 6:542-550. | Outcome
79. | Hosler, AS, Rajulu, DT, Fredrick, BL, Ronsani, AE. Assessing retail fruit and vegetable availability in urban and rural underserved communities. Preventing Chronic Disease. 2008. 5: | Data date range
80. | Huffman, WE. Household production and the demand for food and other inputs: U.S. Evidence. Journal of Agricultural and Resource Economics. 2011. 36:465-487. | Outcome
81. | Hull, MV, Jagim, AR, Oliver, JM, Greenwood, M, Busteed, DR, Jones, MT. Gender differences and access to a sports dietitian influence dietary habits of collegiate athletes. Journal of the International Society of Sports Nutrition. 2016. 13:doi:10.1186/s12970-016-0149-4. | Outcome
82. | Huyghe, Elke, Verstraeten, Julie, Geuens, Maggie, Van Kerckhove, Anneleen. Clicks as a Healthy Alternative to Bricks: How Online Grocery Shopping Reduces Vice Purchases. Journal of Marketing Research (JMR). 2017. 54:61-74. doi:10.1509/jmr.14.0490. | Country
83. | Idowu, Atinuke O, Omobuwajo, TO, Falade, KO. Production proximate analysis and shelf life studies of ready-to-eat rice and kilishi. African Journal of Food Science. 2010. 4:264-268. | Country
84. | Ilyuk, V, Block, L. The effects of single-serve packaging on consumption closure and judgments of product efficacy. Journal of Consumer Research. 2016. 42:858-878. doi:10.1093/jcr/ucv059. | Outcome
85. | Imtiyaz, H, Soni, P, Yukongdi, V. Investigating the Role of Psychological, Social, Religious and Ethical Determinants on Consumers’ Purchase Intention and Consumption of Convenience Food. Foods. 2021. 10:doi:10.3390/foods10020237. | Country
86. | Ismail, MS, Ver Ploeg, M, Chomitz, VR, Wilde, P. Differences in Food-at-Home Spending for SNAP and Non-SNAP Households Given Geographic Price Variation. Journal of the Academy of Nutrition and Dietetics. 2020. 120:1142-1150.e12. doi:10.1016/j.jand.2019.12.017. | Outcome
87. | Jamal, Ahmad, Peattie, Sue, Peattie, Ken. Ethnic minority consumers’ responses to sales promotions in the packaged food market. Journal of Retailing & Consumer Services. 2012. 19:98-108. doi:10.1016/j.jretconser.2011.10.001. | Country
88. | Jenny Sun, CH, Chiang, FS, Owens, M, Squires, D. Will American consumers pay more for eco-friendly labeled canned tuna? Estimating US consumer demand for canned tuna varieties using scanner data. Marine Policy. 2017. 79:62-69. doi:10.1016/j.marpol.2017.02.006. | Intervention/Exposure
89. | Jilcott, SB, Laraia, BA, Evenson, KR, Ammerman, AS. Perceptions of the community food environment and related influences on food choice among midlife women residing in rural and urban areas: A qualitative analysis. Women and Health. 2009. 49:164-180. doi:10.1080/03630240902915085. | Outcome; Data date range
90. | Jock, BW, Roche, KB, Caldas, SV, Redmond, L, Fleischhacker, S, Gittelsohn, J. Latent class analysis offers insight into the complex food environments of native american communities: Findings from the randomly selected OPREVENT2 trial baseline sample. International Journal of Environmental Research and Public Health. 2020. 17:doi:10.3390/ijerph17041237. | Intervention/Exposure
91. | Jones, SA, Walter, J, Soliah, L, Phifer, JT. Perceived motivators to home food preparation: Focus group findings. Journal of the Academy of Nutrition and Dietetics. 2014. 114:1552-1556. doi:10.1016/j.jand.2014.05.003. | Outcome
92. | KC Healthy Kids. The incidence of the inclusion of food at home preparation in the sales tax base. . 9. | Data date range
93. | Keller, KL, Kuilema, LG, Lee, N, Yoon, J, Mascaro, B, Combes, AL, Deutsch, B, Sorte, K, Halford, JCG. The impact of food branding on children’s eating behavior and obesity. Physiology and Behavior. 2012. 106:379-386. doi:10.1016/j.physbeh.2012.03.011. | Outcome
94. | Kern, DM, Auchincloss, AH, Robinson, LF, Stehr, MF, Pham-Kanter, G. Healthy and Unhealthy Food Prices across Neighborhoods and Their Association with Neighborhood Socioeconomic Status and Proportion Black/Hispanic. Journal of Urban Health. 2017. 94:494-505. doi:10.1007/s11524-017-0168-8. | Outcome
95. | Kim, J, Rabbitt, MP, Tuttle, C. Changes in Low-Income Households’ Spending and Time Use Patterns in Response to the 2013 Sunset of the ARRA-SNAP Benefit. Applied Economic Perspectives and Policy. 2020. 42:777-795. doi:10.1093/aepp/ppz007. | Outcome
96. | Kumar, Arvind. Shopping Orientations and Their Inter-Relatedness: A Study on the Poor for CPGs. Journal of Global Marketing. 2020. 33:289-304. doi:10.1080/08911762.2020.1733729. | Country
97. | Lacy, K, Huffman, WE. Consumer demand for potato products andwillingness-to-pay for low-acrylamide, sulfite-free fresh potatoes and dices: Evidence from lab auctions. Journal of Agricultural and Resource Economics. 2016. 41:116-137. | Outcome
98. | Laguna, L, Gómez, B, Garrido, MD, Fiszman, S, Tarrega, A, Linares, MB. Do Consumers Change Their Perception of Liking, Expected Satiety, and Healthiness of a Product If They Know It Is a Ready-to Eat Meal?. Foods. 2020. 9:doi:10.3390/foods9091257. | Outcome
99. | Lee, Jonq-Ying, Kilmer, RichardL. At-Home Convenience Food Consumption and BMI. 2010. 29. doi:10.22004/ag.econ.56428. | Data date range
100. | Lee, JY, Lin, BH. A Study of the Demand for Convenience Food. Journal of Food Products Marketing. 2013. 19:1-14. doi:10.1080/10454446.2013.739120. | Data date range
101. | Lee, SH, Hoffman, VA, Bleich, SN, Gittelsohn, J. Frequency of Visiting and Food Dollars Spent at Carryouts Among Low-Income, Urban African American Adults. Journal of Hunger and Environmental Nutrition. 2013. 7:459-467. doi:10.1080/19320248.2012.735220. | Outcome
102. | Lin, BH, Dong, D, Carlson, A, Rahko vs.ky, I. Potential dietary outcomes of changing relative prices of healthy and less healthy foods: The case of ready-to-eat breakfast cereals. Food Policy. 2017. 68:77-88. doi:10.1016/j.foodpol.2017.01.004. | Data date range
103. | Liu, Y, Balachander, S. How long has it been since the last deal? Consumer promotion timing expectations and promotional response. Quantitative Marketing and Economics. 2014. 12:85-126. doi:10.1007/s11129-013-9141-3. | Outcome
104. | Locher, JL, Ritchie, CS, Roth, DL, Sen, B, Vickers, KS, Vailas, LI. Food choice among homebound older adults: Motivations and perceived barriers. Journal of Nutrition, Health and Aging. 2009. 13:659-664. doi:10.1007/s12603-009-0194-7. | Outcome
105. | Lodolce, ME, Harris, JL, Schwartz, MB. Sugar as part of a balanced breakfast? What cereal advertisements teach children about healthy Eating. Journal of Health Communication. 2013. 18:1293-1309. doi:10.1080/10810730.2013.778366. | Outcome
106. | Loose, Simone Mueller, Peschel, Anne, Grebitus, Carola. Quantifying effects of convenience and product packaging on consumer preferences and market share of seafood products: The case of oysters. Food Quality and Preference. 2013. 28:492-504. | Country
107. | Lotade-Manje, Justus, Dunn, RichardA, Nayga, RodolfoM, Jr, Sharkey, JosephR. Determinants of Affordability of Healthy Food in the Rural Counties: case of the Brazos Valley Area. The relationship between neighborhood characteristics and the affordability of fresh fruits and vegetables. 2009. 26. doi:10.22004/ag.econ.49511. | Outcome
108. | Lucan, SeanC, Barg, FrancesK, Long, JudithA. Promoters and Barriers to Fruit, Vegetable, and Fast-Food Consumption Among Urban, Low-Income African Americans--A Qualitative Approach. American Journal of Public Health. 2010. 100:631-635. doi:10.2105/AJPH.2009.172692. | Outcome
109. | Marckhgott, Eva, Kamleitner, Bernadette. Matte matters: when matte packaging increases perceptions of food naturalness. Marketing Letters. 2019. 30:167-178. doi:10.1007/s11002-019-09488-6. | Outcome
110. | Martin-Belloso, Olga, Soliva Fortuny, Robert. Advances in fresh-cut fruits and vegetables processing. 2019. | Study design
111. | McDermott, AJ, Stephens, MB. Cost of eating: Whole foods versus convenience foods in a low-income model. Family Medicine. 2010. 42:280-284. | Outcome
112. | McGill, CR, Birkett, A, Fulgonii, VL, III. Healthy Eating Index-2010 and food groups consumed by US adults who meet or exceed fiber intake recommendations NHANES 2001-2010. Food and Nutrition Research. 2016. 60:doi:10.3402/fnr.v60.29977. | Outcome
113. | McLean-Meyinsse, PatriciaE, Taylor, SherviaS, Gager, JanetV. Self-Reported Consumption of Fast-Food Meals by University Students. Journal of Food Distribution Research. 2015. 46:23-29. | Outcome
114. | Melo, G, Zhen, C, Colson, G. Does point-of-sale nutrition information improve the nutritional quality of food choices?. Economics and Human Biology. 2019. 35:133-143. doi:10.1016/j.ehb.2019.07.001. | Intervention/Exposure
115. | Melo, Grace, Rabinowitz, AdamN. Food Choices of SNAP/WIC Participants at Convenience Stores and Larger Stores. 2018. doi:10.22004/ag.econ.273844. | Outcome
116. | Miller, SR, Knudson, WA. Nutrition and Cost Comparisons of Select Canned, Frozen, and Fresh Fruits and Vegetables. American Journal of Lifestyle Medicine. 2014. 8:430-437. doi:10.1177/1559827614522942. | Outcome
117. | Moore, LV, Pinard, CA, Yaroch, AL. Features in Grocery Stores that Motivate Shoppers to Buy Healthier Foods, ConsumerStyles 2014. Journal of Community Health. 2016. 41:812-817. doi:10.1007/s10900-016-0158-x. | Outcome
118. | Morrissey, TW, Jacknowitz, A, Vinopal, K. Local food prices and their associations with children’s weight and food security. Pediatrics. 2014. 133:422-430. doi:10.1542/peds.2013-1963. | Data date range
119. | Muhamad, Ida Idayu, Karim, Norsuhada Abdul. Trends, convenience, and safety issues of ready meals. Minimally Processed Foods. 2015. 105-123. | Study design
120. | Mulik, K, Haynes-Maslow, L. The Affordability of MyPlate: An Analysis of SNAP Benefits and the Actual Cost of Eating According to the Dietary Guidelines. Journal of Nutrition Education and Behavior. 2017. 49:623-631.e1. doi:10.1016/j.jneb.2017.06.005. | Outcome
121. | Muth, MK, Karns, SA, Zmuda, M, Coglaiti, MC, Koyanagi, M, Duffey, K, Dunn, C, Jensen, HH, Gregory, C. Price, nutrition, time, and other trade-offs: A web-based food value analysis application to compare foods at different levels of preparation and processing. Nutrition Today. 2014. 49:176-184. doi:10.1097/NT.0000000000000039. | Outcome
122. | Nakano, S, Washizu, A. Aiming for better use of convenience food: an analysis based on meal production functions at home. J Health Popul Nutr. 2020. 39:3. doi:10.1186/s41043-020-0211-3. | Country
123. | Närvänen, Elina, Saarijärvi, Hannu, Simanainen, Olli. Understanding consumers’ online conversation practices in the context of convenience food. International Journal of Consumer Studies. 2013. 37:569-576. doi:10.1111/ijcs.12021. | Country
124. | Ng, SW, Poti, JM, Popkin, BM. Trends in racial/ethnic and income disparities in foods and beverages consumed and purchased from stores among US households with children, 2000-2013. American Journal of Clinical Nutrition. 2016. 104:750-759. doi:10.3945/ajcn.115.127944. | Outcome
125. | Nicola, Silvana, Fontana, Emanuela. Fresh-cut produce quality: implications for a systems approach. Postharvest handling. 2014. 217-273. | Study design; Publication status
126. | O’Dare Wilson, K. The effect of poverty-influenced, food-related consumer behaviors on obesity: An analysis of the NHANES flexible consumer behavioral module. Social Work in Health Care. 2017. 56:400-411. doi:10.1080/00981389.2017.1279704. | Intervention/Exposure
127. | Olsen, Nina Veflen, Sijtsema, Siet J, Hall, Gunnar. Predicting consumers’ intention to consume ready-to-eat meals. The role of moral attitude. Appetite. 2010. 55:534-539. | Country
128. | Olsen, Nina Veflen. The convenience consumer’s dilemma. British Food Journal. 2012. | Country
129. | Page, R, Montgomery, K, Ponder, A, Richard, A. Targeting children in the cereal aisle: Promotional techniques and content features on ready-to-eat cereal product packaging. American Journal of Health Education. 2008. 39:272-282. doi:10.1080/19325037.2008.10599050. | Data date range
130. | Park, Ji Young, Kim, Ji-Na, Hong, Wan-Soo, Shin, Weon-Sun. Survey on Present Use and Future Demand for the Convenience Food in the Elderly Group. Korean J Community Nutr. 2012. 17:81-90. | Publication language
131. | Payne, C, Niculescu, M. Can healthy checkout end-caps improve targeted fruit and vegetable purchases? Evidence from grocery and SNAP participant purchases. Food Policy. 2018. 79:318-323. doi:10.1016/j.foodpol.2018.03.002. | Outcome
132. | Payne, CR, Niculescu, M, Barney, CE. Consumer consumption intentions of smaller packaged snack variants. International Journal of Consumer Studies. 2014. 38:238-242. doi:10.1111/ijcs.12090. | Outcome
133. | Peltner, Jonas, Thiele, Silke. Convenience-based food purchase patterns: Identification and associations with dietary quality, sociodemographic factors and attitudes. Public health nutrition. 2018. 21:558-570. | Country
134. | Peterson, SL, Dodd, KM, Kim, K, Roth, SL. Food cost perceptions and food purchasing practices of uninsured, low-income, rural adults. Journal of Hunger and Environmental Nutrition. 2010. 5:41-55. doi:10.1080/19320240903578073. | Data date range
135. | Phan, MM, Stodolska, M. What Impacts Leisure Activity and Diet among Immigrants? Mexican Immigrants’ Leisure Participation and Food Patterns in the Midwestern U.S. Leisure Sciences. 2019. doi:10.1080/01490400.2019.1656119. | Outcome
136. | Phil, Harris, Silva, Andrés, Von Hausen, Nicolas, Magaña-Lemus, David. Effect of food insecurity on food purchases at home. Journal of Public Affairs (14723891). 2019. 19:N.PAG-N.PAG. doi:10.1002/pa.1852. | Outcome; Country
137. | Phipps, EJ, Braitman, LE, Stites, SD, Singletary, SB, Wallace, SL, Hunt, L, Axelrod, S, Glanz, K, Uplinger, N. Impact of a rewards-based incentive program on promoting fruit and vegetable purchases. American Journal of Public Health. 2015. 105:166-172. doi:10.2105/AJPH.2013.301752. | Intervention/Exposure; Outcome
138. | Phipps, EJ, Wallace, SL, Stites, SD, Uplinger, N, Brook Singletary, S, Hunt, L, Axelrod, S, Glanz, K, Braitman, LE. Using rewards-based incentives to increase purchase of fruit and vegetables in lower-income households: Design and start-up of a randomized trial. Public Health Nutrition. 2013. 16:936-941. doi:10.1017/S1368980012004934. | Study design
139. | PLATTA, ANNA , PUKSZTA, TOMASZ . ELDERLY PEOPLE‘S PERCEPTION OF NEW AND CONVENIENCE FOODS WITH HEALTH BENEFITS. 2019. 2019:doi:10.22004/ag.econ.293920. | Country
140. | Poti, Jennifer, Mendez, Michelle, Ng, Shu Wen, Popkin, Barry. Are Food Processing and Convenience Linked with the Nutritional Quality of Foods Purchased by US Households?. The FASEB Journal. 2015. 29:587.9. doi:https://doi.org/10.1096/fasebj.29.1_supplement.587.9. | Publication status
141. | Powell, LM, Han, E. The costs of food at home and away from home and consumption patterns among U.S. adolescents. Journal of Adolescent Health. 2011. 48:20-26. doi:10.1016/j.jadohealth.2010.06.006. | Data date range
142. | Rahko vs.ky, Ilya, Jo, Young , Carlson, Andrea . What Drives Consumers to Purchase Convenience Foods?. USDA Blog. 2021. | Country; Other
143. | Restrepo, BJ, Zeballos, E. The effect of working from home on major time allocations with a focus on food-related activities. Review of Economics of the Household. 2020. 18:1165-1187. doi:10.1007/s11150-020-09497-9. | Outcome
144. | Richards, R, Brown, LB, Williams, DP, Eggett, DL. Developing a Questionnaire to Evaluate College Students’ Knowledge, Attitude, Behavior, Self-efficacy, and Environmental Factors Related to Canned Foods. Journal of Nutrition Education and Behavior. 2017. 49:117-124.e1. doi:10.1016/j.jneb.2016.10.004. | Outcome
145. | Rogus, S. Examining the influence of perceived and objective time constraints on the quality of household food purchases. Appetite. 2018. 130:268-273. doi:10.1016/j.appet.2018.08.025. | Outcome
146. | Rohatgi, KW, Tinius, RA, Cade, WT, Steele, EM, Cahill, AG, Parra, DC. Relationships between consumption of ultra-processed foods, gestational weight gain and neonatal outcomes in a sample of US pregnant women. PeerJ. 2017. 2017:doi:10.7717/peerj.4091. | Outcome
147. | Rudi, Jeta, Davis, GeorgeC, You, Wen. The Goods-Time Elasticity of Substitution in Home Food Production for Food Stamp/SNAP Participants. 2012. 2. doi:10.22004/ag.econ.124707. | Publication status
148. | Scharadin, B, Jaenicke, EC. Time spent on childcare and the household Healthy Eating Index. Review of Economics of the Household. 2020. 18:357-386. doi:10.1007/s11150-020-09482-2. | Outcome
149. | Schäufele, I, Janssen, M. How and Why Does the Attitude-Behavior Gap Differ Between Product Categories of Sustainable Food? Analysis of Organic Food Purchases Based on Household Panel Data. Front Psychol. 2021. 12:595636. doi:10.3389/fpsyg.2021.595636. | Country
150. | Sen, Shuvro, Antara, Neel, Sen, Shusmita. Factors influencing consumers’ to Take Ready-made Frozen Food. Current Psychology. 2019. 1-10. doi:10.1007/s12144-019-00201-4. | Country
151. | Senia, MC, Jensen, HH, Zhylye vs.kyy, O. Time in eating and food preparation among single adults. Review of Economics of the Household. 2017. 15:399-432. doi:10.1007/s11150-014-9258-5. | Outcome
152. | Shamim, K, Ahmad, S, Alam, MA. COVID-19 health safety practices: Influence on grocery shopping behavior. J Public Aff. 2021. e2624. doi:10.1002/pa.2624. | Country
153. | Sharkey, JR, Horel, S, Dean, WR. Neighborhood deprivation, vehicle ownership, and potential spatial access to a variety of fruits and vegetables in a large rural area in Texas. International Journal of Health Geographics. 2010. 9:doi:10.1186/1476-072X-9-26. | Data date range
154. | Sheely, M. Global adoption of convenience foods. American Journal of Agricultural Economics. 2008. 90:1356-1365. doi:10.1111/j.1467-8276.2008.01231.x. | Data date range
155. | Shen, W, Long, LM, Shih, CH, Ludy, MJ. A humanities-based explanation for the effects of emotional eating and perceived stress on food choice motives during the COVID-19 pandemic. Nutrients. 2020. 12:1-18. doi:10.3390/nu12092712. | Outcome
156. | Short, Gianna, Peterson, Hikaru. Does time spent preparing food affect consumers’ food choices?. 2016. doi:10.22004/ag.econ.244990. | Data date range
157. | Smith, LP, Ng, SW, Popkin, BM. Trends in US home food preparation and consumption: Analysis of national nutrition surveys and time use studies from 1965-1966 to 2007-2008. Nutrition Journal. 2013. 12:doi:10.1186/1475-2891-12-45. | Outcome
158. | Song, HJ, Simon, JR, Patel, DU. Food Preferences of Older Adults in Senior Nutrition Programs. Journal of Nutrition in Gerontology and Geriatrics. 2014. 33:55-67. doi:10.1080/21551197.2013.875502. | Outcome; Other
159. | Speight, KC, Schiano, AN, Harwood, WS, Drake, MA. Consumer insights on prepackaged Cheddar cheese shreds using focus groups, conjoint analysis, and qualitative multivariate analysis. Journal of Dairy Science. 2019. 102:6971-6986. doi:10.3168/jds.2018-16209. | Intervention/Exposure; Outcome
160. | Stallings, TL, Gazmararian, JA, Goodman, M, Kleinbaum, D. Agreement between the perceived and actual fruit and vegetable nutrition environments among low-income Urban women. Journal of Health Care for the Poor and Underserved. 2015. 26:1304-1318. doi:10.1353/hpu.2015.0109. | Outcome
161. | Stanley, K. Frugal cooking. Using canned goods. Diabetes self-management. 2010. 27:17-20. | Publication status
162. | Sutin, A, Robinson, E, Daly, M, Terracciano, A. Weight discrimination and unhealthy eating-related behaviors. Appetite. 2016. 102:83-89. doi:10.1016/j.appet.2016.02.016. | Outcome
163. | Taber, DR, Chriqui, JF, Chaloupka, FJ. State laws governing school meals and disparities in fruit/vegetable intake. American Journal of Preventive Medicine. 2013. 44:365-372. doi:10.1016/j.amepre.2012.11.038. | Outcome
164. | Taillie, LS, Ng, SW, Popkin, BM. Global growth of “big box” stores and the potential impact on human health and nutrition. Nutrition Reviews. 2016. 74:83-97. doi:10.1093/nutrit/nuv062. | Outcome
165. | Tate, EB, Unger, JB, Chou, CP, Spruijt-Metz, D, Pentz, MA, Riggs, NR. Children’s Executive Function and High-Calorie, Low-Nutrient Food Intake: Mediating Effects of Child-Perceived Adult Fast Food Intake. Health Education and Behavior. 2015. 42:163-170. doi:10.1177/1090198114547811. | Outcome
166. | Tripathi, Jyoti, Gupta, Sumit, Kumar, Vivekanand, Chatterjee, Suchandra, Variyar, Prasad S, Sharma, Arun. Processing Food for Convenience: Challenges and Potentials. . | Outcome
167. | Trudel, R, Murray, KB, Kim, S, Chen, S. The impact of traffic light color-coding on food health perceptions and choice. Journal of Experimental Psychology: Applied. 2015. 21:255-275. doi:10.1037/xap0000049. | Outcome
168. | Tu, Juan, Qiu, Feng, Yang, Meng. The value of healthy eating vs.. the value of convenience: Investigating the willingness to pay for living in food swamps. 2020. doi:10.22004/ag.econ.304260. | Publication status
169. | Untari, Asih, Safira, Anya. DETERMINANTS OF NON-MUSLIM CONSUMERS’ PURCHASE BEHAVIOR TOWARD HALAL PACKAGED FOOD. ASEAN Marketing Journal. 2020. 12:60-68. doi:10.21002/amj.v12i1.12892. | Country
170. | Vadiveloo, MK, Parker, HW, Juul, F, Parekh, N. Sociodemographic differences in the dietary quality of food-at-home acquisitions and purchases among participants in the U.S. nationally representative food acquisition and purchase survey (foodaps). Nutrients. 2020. 12:1-18. doi:10.3390/nu12082354. | Outcome
171. | Variyam, JN. Do nutrition labels improve dietary outcomes?. Health Economics. 2008. 17:695-708. doi:10.1002/hec.1287. | Data date range
172. | Vickner, StevenS. Estimating the Implicit Price of Convenience: A Hedonic Analysis of the US Breakfast Sausage Market. Agribusiness. 2015. 31:281-292. doi:10.1002/agr.21404. | Outcome
173. | Vidal, Leticia, Ares, Gastón, Giménez, Ana. Projective techniques to uncover consumer perception: Application of three methodologies to ready-to-eat salads. Food Quality and Preference. 2013. 28:1-7. doi:https://doi.org/10.1016/j.foodqual.2012.08.005. | Country
174. | Webb, R. Healthy eating. Canned heat. A simple broth becomes a delicious meal. Diabetes forecast. 2008. 61: | Study design; Publication status
175. | Wells, Pamela, Dunn-Jensen, LindaM, Yang, Inae. But I Can’t Eat That: Should Babcock Ice Cream Change its Ingredients?. Journal of Critical Incidents. 2019. 12:23-26. | Outcome; Study design
176. | Wetherill, MS, Williams, MB, Taniguchi, T, Salvatore, AL, Jacob, T, Cannady, T, Grammar, M, Standridge, J, Fox, J, Spiegel, J, Blue Bird Jernigan, V. A Nutrition Environment Measure to Assess Tribal Convenience Stores: The THRIVE Study. Health Promotion Practice. 2020. 21:410-420. doi:10.1177/1524839918800968. | Outcome
177. | Wilde, P, Ismail, M, Ver Ploeg, M. The Quality of the Food Retail Environment When Consumers May Be Mobile. Applied Economic Perspectives and Policy. 2021. 43:701-715. doi:10.1002/aepp.13147. | Outcome
178. | Williams, BM, O’Neil, CE, Keast, DR, Cho, S, Nicklas, TA. Ready-to-Eat Cereal Breakfasts Are Associated with Improved Nutrient Intake and Dietary Adequacy but Not Body Mass Index in Black Adolescents. American Journal of Lifestyle Medicine. 2009. 3:500-508. doi:10.1177/1559827609342063. | Data date range
179. | Williams, MB, Wang, W, Taniguchi, T, Salvatore, AL, Groover, WK, Wetherill, M, Love, C, Cannady, T, Grammar, M, Standridge, J, Fox, J, Jernigan, VBB. Impact of a Healthy Retail Intervention on Fruits and Vegetables and Total Sales in Tribally Owned Convenience Stores: Findings From the THRIVE Study. Health Promotion Practice. 2020. doi:10.1177/1524839920953122. | Outcome
180. | Wilson, NLW, Just, DR, Swigert, J, Wansink, B. Food pantry selection solutions: A randomized controlled trial in client-choice food pantries to nudge clients to targeted foods. Journal of Public Health (United Kingdom). 2017. 39:366-372. doi:10.1093/pubmed/fdw043. | Outcome
181. | Wolf, RL, Lepore, SJ, Vandergrift, JL, Wetmore-Arkader, L, McGinty, E, Pietrzak, G, Yaroch, AL. Knowledge, Barriers, and Stage of Change as Correlates of Fruit and Vegetable Consumption among Urban and Mostly Immigrant Black Men. Journal of the American Dietetic Association. 2008. 108:1315-1322. doi:10.1016/j.jada.2008.05.011. | Outcome
182. | Yan, D, Sengupta, J, Wyer Jr, RS. Package size and perceived quality: The intervening role of unit price perceptions. Journal of Consumer Psychology. 2014. 24:4-17. doi:10.1016/j.jcps.2013.08.001. | Country
183. | Yi, Na-Young, Choi, Bo-Ram, Chang, Hye-Ja. Opinion of commercialization of ready-to-eat Korean foods by food-related lifestyle segments in Koreans and non-Koreans. Journal of the Korean Society of Food Science and Nutrition. 2016. 45:602-612. | Country
184. | Yoon, Sungeun, Gao, Zhifeng, House, LisaA. Analysis of Healthy and Convenient Food: The Example of Meal Kit Delivery Services. 2019. doi:10.22004/ag.econ.290854. | Publication status
185. | Zarychta, K, Banik, A, Kulis, E, Boberska, M, Radtke, T, Chan, CKY, Lobczowska, K, Luszczynska, A. Do Parent-Child Dyads with Excessive Body Mass Differ from Dyads with Normal Body Mass in Perceptions of Obesogenic Environment?. Nutrients. 2020. 12:doi:10.3390/nu12072149. | Outcome; Country
186. | Zeballos, E, Mancino, L, Lin, BH. Does how you pay influence the share of healthy items that you Buy? Assessing differences in nutritional quality of food purchases by payment type. Food Policy. 2020. 92:doi:10.1016/j.foodpol.2020.101886. | Outcome
187. | Zhen, C, Finkelstein, EA, Karns, SA, Leibtag, E, Zhang, C. Scanner Data-Based Panel Price Indexes. Am J Agric Econ. 2019. 101:311-329. doi:10.1093/ajae/aay032. | Outcome
188. | Zheng, Yuqing, Dong, Diansheng, Burney, Shaheer, Kaiser, HarryM. Eat at Home or Away from Home? The Role of Grocery and Restaurant Food Sales Taxes. 2019. 44:doi:10.22004/ag.econ.281315. | Intervention/Exposure
189. | Zhu, C, Lopez, RA, Liu, X. Information Cost and Consumer Choices of Healthy Foods. American Journal of Agricultural Economics. 2016. 98:41-53. doi:10.1093/ajae/aav057. | Intervention/Exposure
190. | Zhylye vs.kyy, O, Jensen, HH, Garasky, SB, Cutrona, CE, Gibbons, FX. Effects of family, friends, and relative prices on fruit and vegetable consumption by African Americans. Southern Economic Journal. 2013. 80:226-251. doi:10.4284/0038-4038-2011.277. | Outcome; Data date range