# Appendix 5-a Literature search strategy for the evidence scan on factors that influence the purchase and/or consumption of convenience foods

Database: PubMed

Vendor: National Library of Medicine

Date of Search: 5/20/2021

Limits Used: Filters: Language English Publication Dates 2008 - 2021

Total = 3,201

Search # | Concept | Search String | N
#1 | Convenience Foods | (((“ready to eat”[tiab] OR “ready to heat”[tiab] OR “ready to cook”[tiab] OR “ready to bake”[tiab] OR “pre prepared”[tiab] OR preprepared[tiab] OR “pre made”[tiab] OR; premade[tiab] OR “pre cooked”[tiab] OR precooked[tiab] OR “pre cut”[tiab] OR precut[tiab] OR “fresh cut”[tiab] OR boxed[tiab] OR frozen[tiab] OR canned[tiab] OR dehydrated[tiab] OR tinned[tiab] OR bagged[tiab] OR jarred[tiab] OR “ready made”[tiab] OR instant[tiab] OR prepackaged[tiab] OR “pre-packaged”[tiab] OR “shelf stable”[tiab] OR “single serve”[tiab] OR “single serving”[tiab] OR “pre washed”[tiab] OR prewashed[tiab] OR “partially prepared”[tiab] OR packaged[tiab] OR “easy to prepare”[tiab]); AND; (food[MeSH] OR food*[tiab] OR goods[tiab] OR meal*[tiab] OR snack*[tiab] OR fruit*[tiab] OR vegetable*[tiab])); OR; (“convenient food*”[tiab] OR “convenience food*”[tiab] OR “convenience meal*”[tiab] OR “ready meal”[tiab] OR “food at home”[tiab] OR “fresh cut produce”[tiab])) | 16,186
#2 | | #1 NOT (letter[ptyp] OR editorial[ptyp] OR comment[ptyp] OR news[ptyp] OR “Congress”[Publication Type] OR “Consensus Development Conference”[Publication Type] OR editorial[tiab] OR commentary[tiab] OR “conference abstract*”[tiab] OR “systematic review*”[ti] OR “meta-analysis”[ptyp] OR “meta-analysis”[ti] OR “meta-analyses”[ti] OR “Review”[Publication Type] OR “Systematic Review”[Publication Type] OR “conference proceeding*”[tiab] OR “retracted publication”[ptyp] OR “retraction of publication”[ptyp] OR “retraction of publication”[tiab] OR “retraction notice”[ti] OR “retracted publication”[tiab] OR “Published Erratum”[Publication Type] OR corrigenda[tiab] OR corrigendum[tiab] OR errata[tiab] OR erratum[tiab] OR protocol[ti] OR protocols[ti] OR “case report”[ti] OR “case series”[ti] OR “Case Reports” [Publication Type]); NOT; (“Developing Countries”[Mesh] OR “developing countr*” OR “Under Developed Nation*” OR “low income countr*” OR “middle income countr*”OR “low-middle-income countr*” OR LMIC[tiab] OR “Europe”[Mesh] OR “Australia”[Mesh] OR “Asia”[Mesh] OR “Africa”[Mesh] OR “Mexico”[Mesh] OR “Islands”[Mesh] OR “Central America”[Mesh] OR “Latin America”[Mesh] OR “South America”[Mesh]); ); NOT; (“Animals”[Mesh] NOT; (“Animals”[Mesh] AND “Humans”[Mesh]); ) Filters: English, from 2008 - 2021 | 3,201

Database: Business Source Premiere

Vendor: EBSCO

Date of Search: 5/20/2021

Limits Used: Scholarly (Peer Reviewed) Journals; Published Date: 20080101-20211231; Document Type: Article; Language: English

Total = 6,181

Search # | Concept | Search String | N
#1 | Convenience Foods | (((“ready to eat” OR “ready to heat” OR “ready to cook” OR “ready to bake” OR “pre prepared” OR preprepared OR “pre made” OR premade OR “pre cooked” OR precooked OR “pre cut” OR precut OR “fresh cut” OR boxed OR frozen OR canned OR dehydrated OR tinned OR bagged OR jarred OR “ready made” OR instant OR prepackaged OR “pre-packaged” OR “shelf stable” OR “single serve” OR “single serving” OR “pre washed” OR prewashed OR “partially prepared” OR packaged OR “easy to prepare”); AND; (food* OR goods OR meal* OR snack* OR fruit* OR vegetable*)); OR; (“convenient food*” OR “convenience food*” OR “convenience meal*” OR “ready meal*” OR “food at home” OR “fresh cut produce”)) | 107,790
#2 | | Limiters - Scholarly (Peer Reviewed) Journals; Published Date: 20080101-20211231; Document Type: Article; Language: English | 6,181

Database: Scopus

Vendor: Elsevier

Date of Search: 5/19/2021

Limits Used: Year, Document Type, Source Type, Country/Territory:, Language: English

Total = 4,114

Search # | Concept | Search String | N
#1 | Convenience Foods | TITLE-ABS-KEY ( “convenience food” OR “convenient food” OR “ready meal” OR “convenience meal” OR “food at home” OR “fresh cut produce” ); OR ( TITLE-ABS-KEY ( “ready to eat” OR “ready to heat” OR “ready to cook” OR “ready to bake” OR “pre prepared” OR preprepared OR “pre made” OR premade OR “pre cooked” OR precooked OR “pre cut” OR precut OR “fresh cut” OR boxed OR frozen OR canned OR dehydrated OR tinned OR bagged OR jarred OR “ready made” OR instant OR “pre packaged” OR prepackaged OR “shelf stable” OR “single serve” OR “single serving” OR “pre washed” OR prewashed OR “partially prepared” OR packaged OR “easy to prepare” ); AND TITLE-ABS-KEY ( food OR goods OR meal OR snack OR fruit OR vegetable ) ) | 40,946
#2 | Limiters | ( LIMIT-TO ( PUBYEAR , 2021 ) OR LIMIT-TO ( PUBYEAR , 2020 ) OR LIMIT-TO ( PUBYEAR , 2019 ) OR LIMIT-TO ( PUBYEAR , 2018 ) OR LIMIT-TO ( PUBYEAR , 2017 ) OR LIMIT-TO ( PUBYEAR , 2016 ) OR LIMIT-TO ( PUBYEAR , 2015 ) OR LIMIT-TO ( PUBYEAR , 2014 ) OR LIMIT-TO ( PUBYEAR , 2013 ) OR LIMIT-TO ( PUBYEAR , 2012 ) OR LIMIT-TO ( PUBYEAR , 2011 ) OR LIMIT-TO ( PUBYEAR , 2010 ) OR LIMIT-TO ( PUBYEAR , 2009 ) OR LIMIT-TO ( PUBYEAR , 2008 ) ); AND ( LIMIT-TO ( DOCTYPE , “ar” ); AND ( LIMIT-TO ( AFFILCOUNTRY , “United States” ) OR LIMIT-TO ( AFFILCOUNTRY , “Undefined” ); AND ( LIMIT-TO ( SRCTYPE , “j” ) OR LIMIT-TO ( SRCTYPE , “Undefined” ); AND ( LIMIT-TO ( LANGUAGE , “English” ) | 4,114

## Grey Literature Search

### Google Scholar

Convenience “ready meal” OR “food at home” OR “fresh cut produce” OR “ready to eat” OR “ready to heat” OR “ready to cook” OR “ready to bake” OR “pre made” OR premade OR “pre cooked” OR “pre cut” OR precut OR “fresh cut” OR boxed OR frozen OR canned OR dehydrated OR tinned OR bagged OR jarred OR “ready made” OR instant OR “pre packaged” OR prepackaged OR “shelf stable” OR “single serve” OR “single serving” OR “pre washed” OR prewashed OR “partially prepared” OR packaged OR “easy to prepare”

Limits: Publication Date: 2008-2021;

Date Searched: 5/26/2021

Results: 110, limited to 11 pages

### Google

site:.gov AND Convenience AND “ready meal” OR “food at home” OR “fresh cut produce” OR “ready to eat” OR “ready to heat” OR “ready to cook” OR “ready to bake” OR “pre made” OR premade OR “pre cooked” OR “pre cut” OR precut OR “fresh cut” OR boxed OR frozen OR canned OR dehydrated OR tinned OR bagged OR jarred OR “ready made” OR instant OR “pre packaged” OR prepackaged OR “shelf stable” OR “single serve” OR “single serving” OR “pre washed” OR prewashed OR “partially prepared” OR packaged OR “easy to prepare”

Limits:

Date Searched: 5/27/2021

Results: 30, limited to 3 pages

### Ag Econ

Any of the words: “ready to eat” “ready to heat” “ready to cook” “ready to bake” “pre prepared” preprepared “pre made” premade “pre cooked” precooked “pre cut” precut “fresh cut” boxed frozen canned dehydrated tinned bagged jarred “ready made” instant “pre packaged” prepackaged “shelf stable” “single serve” “single serving” “pre washed” prewashed “partially prepared” packaged “easy to prepare”

AND

Any of the words: food goods meal snack fruit vegetable

OR

Any of the words: “convenience food” “convenient food” “ready meal” “convenience meal” “food at home” “fresh cut produce”

Limits: Added since 2008

Date Searched: 5/26/2021

Results: 120, limited to 12 pages