# Appendix 4-b Excluded articles for the rapid review on income and time spent on food-at-home-related activities

The following table lists the articles excluded after full-text screening for this rapid review question. At least 1 reason for exclusion is provided for each article, though this may not reflect all possible reasons. Information about articles excluded after title and abstract screening is available upon request.

| Bibliography | Rationale for exclusion
1 | Álvarez, Begoña,Miles-Touya, Daniel. Gender imbalance in housework allocation: a question of time?. Review of Economics of the Household. 2019. 17. doi: 10.1007/s11150-019-09467-w. | Country; Outcome
2 | Archer, E.,Shook, R. P.,Thomas, D. M.,Church, T. S.,Katzmarzyk, P. T.,Hébert, J. R.,McIver, K. L.,Hand, G. A.,Lavie, C. J.,Blair, S. N.. 45-Year trends in women’s use of time and household management energy expenditure. PLoS One. 2013. 8. doi: 10.1371/journal.pone.0056620. | Comparator; Outcome
3 | Beatty, T. K.,Nanney, M. S.,Tuttle, C.. Time to eat? The relationship between food security and food-related time use. Public Health Nutr. 2014. 17. doi: 10.1017/s1368980012005599. | Exposure
4 | Beshara, M.,Hutchinson, A.,Wilson, C.. Preparing meals under time stress. The experience of working mothers. Appetite. 2010. 55. doi: 10.1016/j.appet.2010.10.003. | Country
5 | Biddle, Jeff E.,Hamermesh, Daniel S.. Income, wages and household production theory. Economics Letters. 2020. 192. doi: 10.1016/j.econlet.2020.109188. | Date; Outcome
6 | Blitstein, Jonathan L.,Frentz, Florentine,Jilcott Pitts, Stephanie B.. A Mixed-method Examination of Reported Benefits of Online Grocery Shopping in the United States and Germany: Is Health a Factor?. Journal of Food Products Marketing. 2020. 26. doi: 10.1080/10454446.2020.1754313. | Exposure
7 | Bostic, S. M.,McClain, A. C.. Older adults’ cooking trajectories: shifting skills and strategies. British Food Journal. 2017. 119. doi: 10.1108/bfj-09-2016-0436. | Outcome
8 | Bowen, Sarah,Elliott, Sinikka,Brenton, Joslyn. The Joy of Cooking?. Contexts. 2014. 13. doi: 10.1177/1536504214545755. | Comparator
9 | Carpio, C. E.,Kalenkoski, C. M.,Moyeda-Carabaza, A. F.,Murimi, M.. The effect of time use and food cost on dietary quality. Public Health Nutrition. 2020. 23. doi: 10.1017/s1368980020001615. | Comparator
10 | Cason-Wilkerson, R.,Goldberg, S.,Albright, K.,Allison, M.,Haemer, M.. Factors influencing healthy lifestyle changes: a qualitative look at low-income families engaged in treatment for overweight children. Child Obes. 2015. 11. doi: 10.1089/chi.2014.0147. | Outcome
11 | Cawley, J.,Liu, F.. Maternal employment and childhood obesity: a search for mechanisms in time use data. Econ Hum Biol. 2012. 10. doi: 10.1016/j.ehb.2012.04.009. | Exposure; Date
12 | Christian, T. J.. Trade-offs between commuting time and health-related activities. J Urban Health. 2012. 89. doi: 10.1007/s11524-012-9678-6. | Date; Comparator
13 | Connelly, Rachel,Kimmel, Jean. Spousal Economic Factors in ATUS Parents’ Time Choices. Social Indicators Research. 2009. 93. doi: 10.1007/s11205-008-9403-8. | Date; Outcome
14 | Connelly, Rachel,Kimmel, Jean. Spousal influences on parents’ non-market time choices. Review of Economics of the Household. 2009. 7. doi: 10.1007/s11150-009-9060-y. | Date; Outcome
15 | Daniels, S.,Glorieux, I.,Minnen, J.,van Tienoven, T. P.,Weenas, D.. Convenience on the menu? A typological conceptualization of family food expenditures and food-related time patterns. Soc Sci Res. 2015. 51. doi: 10.1016/j.ssresearch.2014.09.010. | Date; Country
16 | Datar, A.,Nicosia, N.,Shier, V.. Maternal work and children’s diet, activity, and obesity. Soc Sci Med. 2014. 107. doi: 10.1016/j.socscimed.2013.12.022. | Exposure; Outcome
17 | Davis, G. C.,You, W.. The Thrifty Food Plan is not thrifty when labor cost is considered. J Nutr. 2010. 140. doi: 10.3945/jn.109.119594. | Date; Study Design; Outcome
18 | Davis, G. C.,You, W.. Estimates of returns to scale, elasticity of substitution, and the thrifty food plan meal poverty rate from a direct household meal production function. Food Policy. 2013. 43. doi: 10.1016/j.foodpol.2013.09.002. | Date
19 | Davis, G. C.,You, W.. Not enough money or not enough time to satisfy the Thrifty Food Plan? A cost difference approach for estimating a money-time threshold. Food Policy. 2011. 36. doi: 10.1016/j.foodpol.2010.09.001. | Date; Exposure; Outcome
20 | Davis, George C.,You, Wen. The time cost of food at home: general and food stamp participant profiles. Applied Economics. 2010. 42. doi: 10.1080/00036840801964468. | Date; Exposure
21 | De Backer, Charlotte J. S.. Family meal traditions. Comparing reported childhood food habits to current food habits among university students. Appetite. 2013. 69. doi: https://doi.org/10.1016/j.appet.2013.05.013. | Outcome; Country
22 | Devine, C. M.,Farrell, T. J.,Blake, C. E.,Jastran, M.,Wethington, E.,Bisogni, C. A.. Work Conditions and the Food Choice Coping Strategies of Employed Parents. Journal of Nutrition Education and Behavior. 2009. 41. doi: 10.1016/j.jneb.2009.01.007. | Outcome
23 | Do, B.,Wang, S. D.,Naya, C. H.,Dunton, G. F.,Mason, T. B.. Momentary and personal characteristics predicting maternal fruit and vegetable preparation for children using ecological momentary assessment. Eat Behav. 2021. 41. doi: 10.1016/j.eatbeh.2021.101492. | Outcome
24 | Dong, K. R.,Tang, A. M.,Stopka, T. J.,Beckwith, C. G.,Must, A.. Food acquisition methods and correlates of food insecurity in adults on probation in Rhode Island. PLoS One. 2018. 13. doi: 10.1371/journal.pone.0198598. | Outcome
25 | Dunaway, L. F.,Carton, T.,Ma, P.,Mundorf, A. R.,Keel, K.,Theall, K. P.. Beyond Food Access: The Impact of Parent-, Home-, and Neighborhood-Level Factors on Children’s Diets. International Journal of Environmental Research and Public Health. 2017. 14. doi: 10.3390/ijerph14060662. | Outcome
26 | Escoto, K. H.,Laska, M. N.,Larson, N.,Neumark-Sztainer, D.,Hannan, P. J.. Work Hours and Perceived Time Barriers to Healthful Eating Among Young Adults. American Journal of Health Behavior. 2012. 36. doi: 10.5993/ajhb.36.6.6. | Exposure
27 | Farmer, N.,Wallen, G. R.,Yang, L.,Middleton, K. R.,Kazmi, N.,Powell-Wiley, T. M.. Household Cooking Frequency of Dinner Among Non-Hispanic Black Adults is Associated with Income and Employment, Perceived Diet Quality and Varied Objective Diet Quality, HEI (Healthy Eating Index): NHANES Analysis 2007-2010. Nutrients. 2019. 11. doi: 10.3390/nu11092057. | Outcome
28 | Fisher, Kimberly,Robinson, John. Average Weekly Time Spent in 30 Basic Activities Across 17 Countries. Social Indicators Research. 2009. 93. doi: 10.1007/s11205-008-9372-y. | Exposure
29 | Gelber, Alexander M.,Mitchell, Joshua W.. Taxes and Time Allocation: Evidence from Single Women and Men. Review of Economic Studies. 2012. 79. doi: 10.1093/restud/rdr041. | Date
30 | Gershuny, Jonathan,Harms, Teresa Atttracta. Housework Now Takes Much Less Time: 85 Years of US Rural Women’s Time Use. Social Forces. 2016. 95. doi: 10.1093/sf/sow073. | Exposure
31 | Graesch, Anthony. Material Indicators of Family Busyness. Social Indicators Research. 2009. 93. doi: 10.1007/s11205-008-9408-3. | Outcome
32 | Gupta, Nabanita Datta,Stratton, Leslie S.. Examining the impact of alternative power measures on individual time use in American and Danish couple households. Review of Economics of the Household. 2010. 8. doi: 10.1007/s11150-009-9073-6. | Date; Exposure
33 | Gupta, Sanjiv,Ash, Michael. Whose money, whose time? A nonparametric approach to modeling time spent on housework in the United States. Feminist Economics. 2008. 14. doi: 10.1080/13545700701716664. | Date; Outcome
34 | Henry, J. L.,Trude, A. C. B.,Surkan, P. J.,Steeves, E. A.,Hopkins, L. C.,Gittelsohn, J.. Psychosocial Determinants of Food Acquisition and Preparation in Low-Income, Urban African American Households. Health Education & Behavior. 2018. 45. doi: 10.1177/1090198118760686. | Outcome
35 | Hobbes, Marieke,De Groot, Wouter T.,Van Der Voet, Ester,Sarkhel, Sukanya. Freely Disposable Time: A Time and Money Integrated Measure of Poverty and Freedom. World Development. 2011. 39. doi: 10.1016/j.worlddev.2011.04.005. | Country; Study Design
36 | Horning, M. L.,Fulkerson, J. A.,Friend, S. E.,Story, M.. Reasons Parents Buy Prepackaged, Processed Meals: It Is More Complicated Than “I Don’t Have Time”. J Nutr Educ Behav. 2017. 49. doi: 10.1016/j.jneb.2016.08.012. | Outcome
37 | Jarrett, R. L.,Bahar, O. S.,Kersh, R. T.. “When We Do Sit Down Together”: Family Meal Times in Low-Income African American Families With Preschoolers. Journal of Family Issues. 2016. 37. doi: 10.1177/0192513x14547417. | Outcome
38 | Kant, A. K.,Graubard, B. I.. Family income and education were related with 30-year time trends in dietary and meal behaviors of American children and adolescents. J Nutr. 2013. 143. doi: 10.3945/jn.112.165258. | Date; Comparator; Outcome
39 | Kolodinsky, J. M.,Goldstein, A. B.. Time use and food pattern influences on obesity. Obesity (Silver Spring). 2011. 19. doi: 10.1038/oby.2011.130. | Exposure
40 | Kolpashnikova, Kamila. American Househusbands: New Time Use Evidence of Gender Display, 2003-2016. Social Indicators Research. 2018. 140. doi: 10.1007/s11205-017-1813-z. | Exposure
41 | Kornides, M. L.,Nansel, T. R.,Quick, V.,Haynie, D. L.,Lipsky, L. M.,Laffel, L. M.,Mehta, S. N.. Associations of family meal frequency with family meal habits and meal preparation characteristics among families of youth with type 1 diabetes. Child Care Health Dev. 2014. 40. doi: 10.1111/cch.12078. | Outcome
42 | Kornrich, S.,Roberts, A.. Household Income, Women’s Earnings, and Spending on Household Services, 1980-2010. Journal of Marriage and Family. 2018. 80. doi: 10.1111/jomf.12450. | Date; Outcome
43 | Landefeld, J. Steven,Fraumeni, Barbara M.,Vojtech, Cindy M.. ACCOUNTING FOR HOUSEHOLD PRODUCTION: A PROTOTYPE SATELLITE ACCOUNT USING THE AMERICAN TIME USE SURVEY. Review of Income & Wealth. 2009. 55. doi: 10.1111/j.1475-4991.2009.00319.x. | Date; Comparator
44 | Ly, D. P.,Jena, A. B.. Sex Differences in Time Spent on Household Activities and Care of Children Among US Physicians, 2003-2016. Mayo Clin Proc. 2018. 93. doi: 10.1016/j.mayocp.2018.02.018. | Exposure; Comparator
45 | Martell, Michael E.,Roncolato, Leanne. Share of Household Earnings and Time Use of Women in Same-Sex and Different-Sex Households. Eastern Economic Journal. 2020. 46. doi: 10.1057/s41302-019-00145-4. | Outcome; Date
46 | McGuirt, J. T.,Wu, Q.,Laska, M. N.,Truesdale, K. P.,Rafferty, A. P.,Bell, R. A.,Ammerman, A. S.,Jilcott Pitts, S. B.. Associations between shopping patterns, dietary behaviours and geographic information system-assessed store accessibility among small food store customers. Public Health Nutr. 2020. . doi: 10.1017/s1368980020005017. | Exposure; Comparator
47 | Milkie, Melissa A.,Raley, Sara B.,Bianchi, Suzanne M.. Taking on the Second Shift: Time Allocations and Time Pressures of U.S. Parents with Preschoolers. Social Forces. 2009. 88. doi: 10.1353/sof.0.0268. | Date; Outcome
48 | Mills, Susanna,Brown, Heather,Wrieden, Wendy,White, Martin,Adams, Jean. Frequency of eating home cooked meals and potential benefits for diet and health: cross-sectional analysis of a population-based cohort study. International Journal of Behavioral Nutrition and Physical Activity. 2017. 14. doi: 10.1186/s12966-017-0567-y. | Country; Outcome
49 | Nepper, M. J.,Chai, W.. Parents’ barriers and strategies to promote healthy eating among school-age children. Appetite. 2016. 103. doi: 10.1016/j.appet.2016.04.012. | Outcome
50 | Neumark-Sztainer, D.,MacLehose, R.,Loth, K.,Fulkerson, J. A.,Eisenberg, M. E.,Berge, J.. What’s for dinner? Types of food served at family dinner differ across parent and family characteristics. Public Health Nutrition. 2014. 17. doi: 10.1017/s1368980012004594. | Comparator; Outcome
51 | Neumark-Sztainer, D.,Wall, M.,Fulkerson, J. A.,Larson, N.. Changes in the frequency of family meals from 1999 to 2010 in the homes of adolescents: trends by sociodemographic characteristics. J Adolesc Health. 2013. 52. doi: 10.1016/j.jadohealth.2012.06.004. | Outcome
52 | Oleschuk, Merin. Expanding the joys of cooking: How class shapes the emotional experience of family foodwork. Gender, Work & Organization. 2020. . doi: 10.1111/gwao.12599. | Country
53 | Pailhé, Ariane,Solaz, Anne,Stanfors, Maria. The Great Convergence: Gender and Unpaid Work in Europe and the United States. Population & Development Review. 2021. 47. doi: 10.1111/padr.12385. | Date
54 | Pelletier, J. E.,Laska, M. N.. Balancing healthy meals and busy lives: associations between work, school, and family responsibilities and perceived time constraints among young adults. J Nutr Educ Behav. 2012. 44. doi: 10.1016/j.jneb.2012.04.001. | Outcome
55 | Pepin, Joanna R.,Sayer, Liana C.,Casper, Lynne M.. Marital Status and Mothers’ Time Use: Childcare, Housework, Leisure, and Sleep. Demography (Springer Nature). 2018. 55. doi: 10.1007/s13524-018-0647-x. | Exposure; Outcome
56 | Quick, B. L.,Fiese, B. H.,Anderson, B.,Koester, B. D.,Marlin, D. W.. A formative evaluation of shared family mealtime for parents of toddlers and young children. Health Commun. 2011. 26. doi: 10.1080/10410236.2011.561920. | Comparator; Outcome
57 | Rogus, S.. Examining the influence of perceived and objective time constraints on the quality of household food purchases. Appetite. 2018. 130. doi: 10.1016/j.appet.2018.08.025. | Outcome
58 | Schneider, Daniel,Hastings, Orestes P.. Income Inequality and Household Labor. Social Forces. 2017. 96. doi: 10.1093/sf/sox061. | Outcome; Date
59 | Sen, Shuvro,Antara, Neel,Sen, Shusmita. Factors influencing consumers’ to Take Ready-made Frozen Food. Current Psychology. 2019. . doi: 10.1007/s12144-019-00201-4. | Country
60 | Smith, L. P.,Ng, S. W.,Popkin, B. M.. Trends in US home food preparation and consumption: analysis of national nutrition surveys and time use studies from 1965-1966 to 2007-2008. Nutr J. 2013. 12. doi: 10.1186/1475-2891-12-45. | Date; Comparator
61 | Sonneville, K. R.,La Pelle, N.,Taveras, E. M.,Gillman, M. W.,Prosser, L. A.. Economic and other barriers to adopting recommendations to prevent childhood obesity: results of a focus group study with parents. BMC Pediatr. 2009. 9. doi: 10.1186/1471-2431-9-81. | Date; Outcome
62 | Starmer, A. J.,Frintner, M. P.,Matos, K.,Somberg, C.,Freed, G.,Byrne, B. J.. Gender Discrepancies Related to Pediatrician Work-Life Balance and Household Responsibilities. Pediatrics. 2019. 144. doi: 10.1542/peds.2018-2926. | Exposure; Outcome
63 | Taillie, L. S.. Who’s cooking? Trends in US home food preparation by gender, education, and race/ethnicity from 2003 to 2016. Nutr J. 2018. 17. doi: 10.1186/s12937-018-0347-9. | Comparator; Outcome
64 | Tao, Hung-Lin. Informational Ambiguity and Survey Bias: Husbands’ and Wives’ Reports on Their Contribution to Their Families. Social Indicators Research. 2013. 111. doi: 10.1007/s11205-012-0029-5. | Country
65 | Tashiro, S.,Lo, C. P.. Gender Difference in the Allocation of Time PREPARING FOOD COOKED AT HOME VERSUS PURCHASING PREPARED FOOD. Food Culture & Society. 2012. 15. doi: 10.2752/175174412x13276629246000. | Date
66 | Tashiro, Sanae. Differences in Food Preparation by Race and Ethnicity: Evidence from the American Time Use Survey. Review of Black Political Economy. 2009. 36. doi: 10.1007/s12114-009-9045-3. | Date
67 | Taveras, E. M.,McDonald, J.,O’Brien, A.,Haines, J.,Sherry, B.,Bottino, C. J.,Troncoso, K.,Schmidt, M. E.,Koziol, R.. Healthy Habits, Happy Homes: methods and baseline data of a randomized controlled trial to improve household routines for obesity prevention. Prev Med. 2012. 55. doi: 10.1016/j.ypmed.2012.08.016. | Exposure; Outcome
68 | Tiedje, K.,Wieland, M. L.,Meiers, S. J.,Mohamed, A. A.,Formea, C. M.,Ridgeway, J. L.,Asiedu, G. B.,Boyum, G.,Weis, J. A.,Nigon, J. A.,Patten, C. A.,Sia, I. G.. A focus group study of healthy eating knowledge, practices, and barriers among adult and adolescent immigrants and refugees in the United States. Int J Behav Nutr Phys Act. 2014. 11. doi: 10.1186/1479-5868-11-63. | Comparator; Outcome
69 | Tiwari, A.,Aggarwal, A.,Tang, W.,Drewnowski, A.. Cooking at Home: A Strategy to Comply With US Dietary Guidelines at No Extra Cost. American Journal of Preventive Medicine. 2017. 52. doi: 10.1016/j.amepre.2017.01.017. | Outcome
70 | Trofholz, A. C.,Tate, A.,Keithahn, H.,de Brito, J. N.,Loth, K.,Fertig, A.,Berge, J. M.. Family meal characteristics in racially/ethnically diverse and immigrant/refugee households by household food security status: A mixed methods study. Appetite. 2021. 157. doi: 10.1016/j.appet.2020.105000. | Outcome
71 | Tuttle, Charlotte. Changes in Food-At-Home Spending by SNAP Participants After the Stimulus Act of 2009. . 2016. . doi: 10.22004/ag.econ.252645. | Outcome
72 | Virudachalam, S.,Chung, P. J.,Faerber, J. A.,Pian, T. M.,Thomas, K.,Feudtner, C.. Quantifying parental preferences for interventions designed to improve home food preparation and home food environments during early childhood. Appetite. 2016. 98. doi: 10.1016/j.appet.2015.11.007. | Outcome
73 | Virudachalam, S.,Long, J. A.,Harhay, M. O.,Polsky, D. E.,Feudtner, C.. Prevalence and patterns of cooking dinner at home in the USA: National Health and Nutrition Examination Survey (NHANES) 2007-2008. Public Health Nutrition. 2014. 17. doi: 10.1017/s1368980013002589. | Date; Outcome
74 | Wolfson, J. A.,Bleich, S. N.,Smith, K. C.,Frattaroli, S.. What does cooking mean to you?: Perceptions of cooking and factors related to cooking behavior. Appetite. 2016. 97. doi: 10.1016/j.appet.2015.11.030. | Outcome
75 | Wolfson, J. A.,Leung, C. W.,Richardson, C. R.. More frequent cooking at home is associated with higher Healthy Eating Index-2015 score. Public Health Nutrition. 2020. 23. doi: 10.1017/s1368980019003549. | Outcome
76 | Wulff Pabilonia, Sabrina,Younghwan, Song. Single Mothers’ Time Preference, Smoking, and Enriching Childcare: Evidence from Time Diaries. Eastern Economic Journal. 2013. 39. doi: 10.1057/eej.2013.7. | Date
77 | Yenerall, J.,You, W.,Hill, J.. Beyond the supermarket: analyzing household shopping trip patterns that include food at home and away from home retailers. BMC Public Health. 2020. 20. doi: 10.1186/s12889-020-09882-0. | Exposure; Outcome
78 | You, W, Davis, G,C,. Household food expenditures, parental time allocation, and childhood overweight: An integrated two-stage collective model with an empirical application and test. American Journal of Agricultural Economics. 2010. 92. doi: 10.1093/ajae/aap031. | Date
79 | Zeballos, Eliana,Restrepo, Brandon. Working From Home Leads to More Time Spent Preparing Food, Eating at Home. . 2021. 2020. doi: 10.22004/ag.econ.309609. | Exposure