# Appendix 0-a Abbreviations

Abbreviation: Full name
ATUS: American Time Use Survey
BMI: Body Mass Index
CACFP: Child and Adult Care Food Program
CNPP: Center for Nutrition Policy and Promotion
CSFII: Continuing Survey of Food Intakes by Individuals II
DGA: Dietary Guidelines for Americans
FNS: Food and Nutrition Service
FSP: Food Stamp Program
HANDLS: Healthy Aging in Neighborhoods of Diversity across the Life Span Study
HEI: Healthy Eating Index
NEAT: Nutrition and Economic Analysis Team
NEMS-S: Nutrition Environment Measures Survey in stores
NESR: Nutrition Evidence Systematic Review team
NGAD: Nutrition Guidance and Analysis Division
NHANES: National Health and Nutrition Examination Survey
NSLP: National School Lunch Program
PCS: Prospective Cohort Study
PICO: Population, Intervention, Comparator, Outcome
PIR: Poverty Index Ratio
RCT: Randomized Controlled Trial
ROB: Risk of bias
RTB: Ready-to-bake
RTC: Ready-to-cook
RTE: Ready-to-eat
RTH: Read-to-heat
RTP: Ready-to-prepare
SBP: School Breakfast Program
SE: Standard Error
SES: Socioeconomic status
SNAP: Supplemental Nutrition Assistance Program
SOS III: Seattle Obesity Study III
SSI: Supplemental Security Income
TFP: Thrifty Food Plan
U.S.: United States
USDA: United States Department of Agriculture
WIC: Special Supplemental Nutrition Program for Women, Infants, and Children