# WHAT IS THE RELATIONSHIP BETWEEN FEEDING A LOWER VERSUS HIGHER INTENSITY, PROPORTION, OR AMOUNT OF HUMAN MILK TO MIXED-FED INFANTS AND CHILDHOOD LEUKEMIA?

## PLAIN LANGUAGE SUMMARY

### What is the question?

- The question is: What is the relationship between feeding a lower versus higher intensity, proportion, or amount of human milk to mixed-fed infants and childhood leukemia?

### What is the answer to the question?

- There is no evidence to determine whether or not there is a relationship between feeding a lower versus higher intensity, proportion, or amount of human milk to mixed-fed infants and childhood leukemia.

### Why was this question asked?

- This important public health question was identified and prioritized as part of the U.S. Department of Agriculture and Department of Health and Human Services Pregnancy and Birth to 24 Months Project.

### How was this question answered?

- A team of Nutrition Evidence Systematic Review staff conducted a systematic review in collaboration with a group of experts called a Technical Expert Collaborative.

### What is the population of interest?

- The population of interest was generally healthy infants and toddlers (ages 0-24 months) who were in studies examining leukemia in childhood (ages 2-12 years).

### What evidence was found?

- No evidence was found to answer this systematic review question.

### How up-to-date is this review?

- This review includes literature from 01/1980 to 03/2016.

## FULL REVIEW

### Systematic review question

What is the relationship between feeding a lower versus higher intensity, proportion, or amount of human milk to mixed-fed infants and childhood leukemia?

### Conclusion statement

There is no evidence to determine whether or not there is a relationship between feeding a lower versus higher intensity, proportion, or amount of human milk to mixed-fed infants and childhood leukemia

### Grade

Grade Not Assignable

### Summary

- This systematic review examines comparisons of mixed-fed infants fed different intensities, proportions, or amounts of human milk. Mixed feeding was defined as feeding human milk and infant formula but not complementary foods or beverages such as cow’s milk. Human milk was defined as mother’s own milk provided at the breast (i.e., nursing) or expressed and fed fresh or after refrigeration or freezing. Donor milk (e.g., banked milk) was not examined in this review. Infant formula was defined as commercially-prepared infant formula meeting FDA^6^ and/or Codex Alimentarius^7^ international food standards. Complementary foods and beverages was defined as foods and beverages other than human milk or infant formula provided to an infant or young child to provide nutrients and energy.
- Childhood leukemia includes acute leukemia, generally, as well as acute lymphoblastic leukemia, specifically.
- No articles published since 1980 met the inclusion criteria for this systematic review

### Research recommendations

Studies need to be designed and conducted to examine the relationship between feeding a lower versus higher intensity, proportion, or amount of human milk to mixed-fed infants and childhood leukemia.

Infant-feeding research will continue to rely on observational designs, because of ethical issues related to randomizing infant to be fed less or no human milk; however, researchers should endeavor to minimize bias through sound research design and conduct. In general, infant-feeding researchers should:

- Move toward collecting data consistently using valid and reliable methods
- Increase the precision with which they define infant-feeding variables
- Incorporate effect modification into their study design whenever possible in case different biological or environmental characteristics modify the impact of infant feeding on the outcomes

## ANALYTIC FRAMEWORK

The analytic framework (Figure 1) illustrates the overall scope of the systematic review, including the population, exposures, comparators, and outcomes of interest. It also includes definitions of key terms and lists critical confounders. This is the analytic framework for the systematic review conducted to examine the relationship between feeding a lower versus higher intensity, proportion, or amount of human milk to mixed-fed infants and childhood leukemia.

Figure 1 Analytic framework

This is the analytic framework for the systematic review conducted to examine the relationship between feeding a lower versus higher intensity, proportion, or amount of human milk to mixed-fed infants and childhood leukemia. The target population is birth through childhood. The exposure is the intensity/proportion/amount of human milk fed to mixed-fed infants both at a given point in time and over a period of time, and the comparator is a higher intensity/proportion/amount of human milk fed to mixed-fed infants. The endpoint health outcome is leukemia (i.e., acute leukemia as well as acute lymphoblastic leukemia, specifically). Mixed feeding is defined as feedin human milk and infant formula but not complementary foods and beverages such as cow's milk. Human milk is defined as mother's own milk provided at the breast or expressed and fed fresh or after refrigeration/freezing. Donor milk (e.g., banked milk) is not examined in this review. Infant formula is defined as commercially-prepared infant formula meeting FDA and/or Codex Alimentarius international food standards. Complementary foods and beverages refers to foods and beverages other than human milk or infant formula that are provided to an infant or young child to provide nutrients and energy.

## SEARCH PLAN AND RESULTS

### Inclusion and exclusion criteria

The inclusion and exclusion criteria (Table 1) are a set of characteristics to determine which studies will be included or excluded in the systematic review. This table provides the inclusion and exclusion criteria for the systematic review question: What is the relationship between feeding a lower versus higher intensity, proportion, or amount of human milk to mixed-fed infants and childhood leukemia?

Table 1 Inclusion and exclusion criteria

Category | Inclusion Criteria | Exclusion Criteria
Study design | Randomized controlled trials; Non-randomized controlled trials; Prospective cohort studies; Retrospective cohort studies; Case-control studies | Cross-sectional studies; Before-and-after studies; Uncontrolled studies; Narrative reviews; Systematic reviews; Meta-analyses
Publication status | Published in peer-reviewed journals | Grey literature, including unpublished data, manuscripts, reports, abstracts, and conference proceedings
Language | Published in English | Published in languages other than English
Date range | Published from 1980-December 2015^8^ | Published prior to 1980
Intervention/exposure | Intensity, proportion, or amount of human milk fed to mixed-fed infants (i.e., infants fed human milk and infant formula but not complementary foods and beverages) at a given point in time or over a period of time | Feeding complementary foods and beverages
Comparator | Higher intensities, proportions, or amounts of human milk fed to mixed-fed infants (i.e., infants fed human milk and infant formula but not complementary foods and beverages) at a given point in time or over a period of time | Feeding complementary foods and beverages
Source of foods, beverages, or nutrients | Human milk: mothers’ own milk (MOM), that is, human milk at the breast (i.e., nursing) or expressed and fed fresh or after refrigeration/freezing; Infant formula: commercially-prepared infant formula meeting FDA^9^ and/or Codex Alimentarius^10^ international food standards | Human milk from third parties (e.g., banked/donor milk); Infant formulas that are not commercially-prepared or that do not meet FDA and/or Codex Alimentarius international food standards
Outcome | Incidence and prevalence of leukemia (i.e., acute leukemia and acute lymphoblastic leukemia) | Other leukemias (e.g., AML), which are less common and less likely to have sufficient statistical power
Study setting | Countries listed as Very High or High on the 2014 Human Development Index^11^ | Countries listed as Medium or Low on the 2014 Human Development Index
Study participants | Human participants; Males; Females | Non-human participants (e.g., animal studies, in vitro studies); Hospitalized patients, not including birth and immediate post-partum hospitalization of healthy babies
Age of study participants | Exposure age: infants (0-12 months), toddlers (12-24 months); Outcome age: children (2-12 years) (i.e., include studies with children within the sample)
Size of study groups | Studies with ≥30 participants per study group or a power analysis indicating that the study is appropriately powered for the outcome(s) of interest | Studies with <30 participants per study group with no power analysis indicating that the study is appropriately powered for the outcome(s) of interest
Health status of study participants | Studies done in generally healthy populations; Studies done in populations where infants were full term (≥37 and 0/7 weeks gestational age); Studies done in populations with elevated chronic disease risk, or that enroll some participants with a disease or with the health outcome of interest | Studies that exclusively enroll participants with a disease or the health outcome of interest; Studies done in hospitalized participants (except for birth and immediate post-partum hospitalization of healthy babies) or malnourished participants; Studies of exclusively pre-term babies (gestational age <37 weeks), exclusively babies that have low birth weight (<2500g) and/or exclusively babies that are small for gestational age

### Search terms and electronic databases used

#### PubMed

- Dates searched: Dec 4, 2015 and March 28, 2016 to refine/limit search terms and remove pub type indexing
- Search Terms:
  (breast feeding[mh] OR breastfeeding[tiab] OR breast feeding*[tiab] OR breast-feeding*[tiab] OR breastfed[tiab] OR breast-fed[tiab] OR breastfeed*[tiab] OR “breast feed”[tiab]) OR (Milk, human[mh] OR “breast milk”[tiab] OR breast-milk[tiab] OR “human milk”[tiab] OR “mother’s milk”[tiab] OR breastmilk[tiab]) OR (Bottle feeding[mh] OR bottle feeding*[tiab] OR “bottle feeding”[tiab] OR bottle-feeding*[tiab] OR bottle-fed[tiab] OR “bottle fed”[tiab])
  NOT ((aids[ti] AND “Acquired Immunodeficiency Syndrome”[Mesh]) OR hiv[ti] OR HIV/AIDS[ti] OR human immunodefic*[ti] OR Acquired Immunodefic*[ti] OR “low birth weight”[ti] OR lbw[ti] OR vlbw[ti] OR elbw[ti] OR pcb[ti] OR pcbs[ti] OR Polychlorinated Biphenyl*[ti] OR Polychlorobiphenyl Compound*[ti] OR dioxin*[ti] OR (breast[ti] AND (tumor*[ti] OR tumour*[ti] OR cancer*[ti] OR carcinoma*[ti] OR disease*[ti]))) NOT (breastfeed*[ti] OR breastfed*[ti] OR feed*[ti] OR fed[ti] OR milk[ti])
  NOT (editorial[ptyp] OR comment[ptyp] OR news[ptyp] OR letter[ptyp] OR review[ptyp] OR systematic[sb])
  Limiters; Engl/humans; 1980-

#### Embase

- Date searched: Dec 5, 2015
- Search Terms:
  ‘bottle feeding’/exp OR ‘bottle feeding’:ab,ti OR ‘bottle feedings’:ab,ti OR ‘bottle fed’:ab,ti OR bottle* NEAR/3 feed* AND [english]/lim AND [humans]/lim AND [1980-2015]/py OR ‘breast milk’/exp OR ‘human milk’:ab,ti OR ‘breast milk’:ab,ti OR breastmilk:ab,ti OR mother* NEAR/2 milk OR ‘maternal milk’:ab,ti AND [english]/lim AND [humans]/lim AND [1980-2015]/py OR ‘breast feeding’/exp OR breastfeed*:ab,ti OR ‘breast feed’:ab,ti OR ‘breast feeding’:ab,ti OR breastfed:ab,ti OR ‘breast fed’:ab,ti OR feeding NEAR/3 breast AND [english]/lim AND [humans]/lim AND [1980-2015]/py
  [underlined: Using Citation manager to filter out title key words:]
  NOT (aids AND “Acquired Immunodeficiency Syndrome”) OR hiv OR HIV/AIDS OR human immunodefic* OR Acquired Immunodefic* OR “low birth weight” OR lbw OR vlbw OR elbw OR pcb OR pcbs OR Polychlorinated Biphenyl* OR Polychlorobiphenyl Compound* OR dioxin* OR (breast AND (tumor* OR tumour* OR cancer* OR carcinoma* OR disease*)) OR preterm OR premature

#### CINAHL

- Date searched: Dec 8, 2015
- Search Terms:
  (MH “Breast Feeding+” OR breast-fed OR “breast fed” OR breastfeeding OR breast feeding OR breast-fed) OR MH “Milk, Human” OR “Human Milk” OR “Breast Milk” OR Breastmilk OR breast-milk OR ((maternal OR mother*) n3 milk) OR (MH “Bottle Feeding”) OR “bottle feeding” OR (bottle n3 feed*) OR bottle-feeding OR bottle-feedings OR “bottle fed” OR “bottle-fed”)
  [underlined: Using Citation manager to filter out title key words:]
  NOT (aids AND “Acquired Immunodeficiency Syndrome”) OR hiv OR HIV/AIDS OR human immunodefic* OR Acquired Immunodefic* OR “low birth weight” OR lbw OR vlbw OR elbw OR pcb OR pcbs OR Polychlorinated Biphenyl* OR Polychlorobiphenyl Compound* OR dioxin* OR (breast AND (tumor* OR tumour* OR cancer* OR carcinoma* OR disease*)) OR preterm OR premature

#### Cochrane

- Date searched: Dec 8, 2015
- Search Terms:
  “Breast Feeding”OR breast-fed OR “breast fed” OR breastfeeding OR “breast feeding” OR “breast feed” OR “breast feeds” OR breast-feed OR breast-feeds OR (breast NEAR/3 feed*) OR “human milk” OR “breast milk” OR breastmilk OR “mother’s milk” OR “maternal milk” OR ((mother* OR maternal OR donor* OR donate*) NEAR/3 milk) OR “Bottle feeding” OR “bottle feedings” OR “bottle-feeding” OR “bottle-feedings” OR (bottle NEAR/3 feed*)
  [underlined: Using Citation manager to filter out title key words:]
  NOT (aids AND “Acquired Immunodeficiency Syndrome”) OR hiv OR HIV/AIDS OR human immunodefic* OR Acquired Immunodefic* OR “low birth weight” OR lbw OR vlbw OR elbw OR pcb OR pcbs OR Polychlorinated Biphenyl* OR Polychlorobiphenyl Compound* OR dioxin* OR (breast AND (tumor* OR tumour* OR cancer* OR carcinoma* OR disease*)) OR preterm OR premature

Figure 2 Flow chart of literature search and screening results

This flow chart illustrates the literature search and screening results for articles examining the relationship between infant milk-feeding practices, including feeding a lower versus higher intensity, proportion, or amount of human milk to mixed-fed infants and several outcomes, including childhood leukemia. The literature search yielded 31,335 articles. During title and abstract screening, 28,537 articles were screened out. During full-text screening, 2,606 articles were screened out. During the hand search, 17 additional articles were identified to include. In total, 0 articles were included in the systematic review on the relationship between feeding a lower versus higher intensity, proportion, or amount of human milk to mixed-fed infants and childhood leukemia.

This flow chart illustrates the literature search and screening results for articles examining the relationship between infant milk-feeding practices, including feeding a lower versus higher intensity, proportion, or amount of human milk to mixed-fed infants, and several outcomes, including childhood leukemia. The results of the electronic database searches were screened independently by two NESR analysts in a step-wise manner by reviewing titles and abstracts, and then full text articles to determine which articles met the criteria for inclusion. A manual search was done to ascertain articles not identified through the electronic database search. The systematic review on feeding a lower versus higher intensity, proportion, or amount of human milk to mixed-fed infants and childhood leukemia included 0 articles.

Table 2 Excluded articles

The table below lists the full-text articles excluded with at least one reason for exclusion, and may not reflect all possible reasons.

| Citation | Reasons for exclusion
1 | Aarts, C.,Kylberg, E.,Hofvander, Y.,Gebre-Medhin, M. Growth under privileged conditions of healthy Swedish infants exclusively breastfed from birth to 4-6 months: a longitudinal prospective study based on daily records of feeding. Acta Paediatr. 2003;92(2):145-51. | Independent variable
2 | Abarin, T.,Yan Wu, Y.,Warrington, N.,Lye, S.,Pennell, C.,Briollais, L. The impact of breastfeeding on FTO-related BMI growth trajectories: an application to the Raine pregnancy cohort study. Int J Epidemiol. 2012;41(6):1650-60. | Independent variable
3 | Abdel-Hafeez, E. H.,Belal, U. S.,Abdellatif, M. Z. M.,Naoi, K.,Norose, K. Breast-feeding protects infantile diarrhea caused by intestinal protozoan infections. Korean Journal of Parasitology. 2013;51(5):519-524. | Health status
4 | Abdoll, G. S. Report on the nursing bottle caries campaign launched by the Free State Oral Health Services. Sadj. 2001;56(1):32-3. | Study design
5 | Abdulmoneim, I.,Al-Ghamdi, S. A. Relationship between breast-feeding duration and acute respiratory infections in infants. Saudi Med J. 2001;22(4):347-50. | Study design
6 | Aberg, N.,Engstrom, I.,Lindberg, U. Allergic diseases in Swedish school children. Acta Paediatr Scand. 1989;78(2):246-52. | Study design
7 | Abraham, E. C.,Godwin, J.,Sherriff, A.,Armstrong, J. Infant feeding in relation to eating patterns in the second year of life and weight status in the fourth year. Public Health Nutr. 2012;15(9):1705-14. | Included for systematic reviews not completed
8 | Abuekteish, F.,Alwash, R.,Hassan, M.,Daoud, A. S. Prevalence of asthma and wheeze in primary school children in northern Jordan. Ann Trop Paediatr. 1996;16(3):227-31. | Study design
9 | Abusaad, Fawzia E.,El-Gilany, Abdel-Hady. Exclusive breastfeeding and infant morbidity in Sakaka City, Saudi Arabia. Middle East Journal of Nursing. 2011;5(6):3-8 6p. | Independent variable, Dependent variable
10 | Academy of Breastfeeding Medicine. ABM Clinical Protocol #24: Allergic Proctocolitis in the Exclusively Breastfed Infant. Breastfeed Med. 2011;6(6):435-40. | Study design
11 | Adgent, M. A.,Hoffman, K.,Goldman, B. D.,Sjodin, A.,Daniels, J. L. Brominated flame retardants in breast milk and behavioural and cognitive development at 36 months. Paediatr Perinat Epidemiol. 2014;28(1):48-57. | Independent variable
12 | Adlakha, A. L.,Suchindran, C. M. Factors affecting infant and child mortality. J Biosoc Sci. 1985;17(4):481-96. | Study design
13 | Agache, I.,Ciobanu, C. Risk factors and asthma phenotypes in children and adults with seasonal allergic rhinitis. Phys Sportsmed. 2010;38(4):81-6. | Study design
14 | Agarwal, D. K.,Agarwal, K. N.,Khare, B. B. Study on current status of infant and childhood feeding practices. Indian Pediatr. 1985;22(9):716. | Study design, Country
15 | Agostoni, C. Breast-feeding, human milk, long-chain polyunsaturated fatty acids and development. Dev Med Child Neurol Suppl. 2001;86:8-9. | Study design
16 | Agostoni, C.,Fiocchi, A.,Riva, E.,Terracciano, L.,Sarratud, T.,Martelli, A.,Lodi, F.,D’Auria, E.,Zuccotti, G.,Giovannini, M. Growth of infants with IgE-mediated cow’s milk allergy fed different formulas in the complementary feeding period. Pediatr Allergy Immunol. 2007;18(7):599-606. | Independent variable, Health status
17 | Agostoni, C.,Grandi, F.,Gianni, M. L.,Silano, M.,Torcoletti, M.,Giovannini, M.,Riva, E. Growth patterns of breast fed and formula fed infants in the first 12 months of life: an Italian study. Arch Dis Child. 1999;81(5):395-9. | Included for systematic reviews not completed
18 | Agostoni, C.,Grandi, F.,Scaglioni, S.,Gianni, M. L.,Torcoletti, M.,Radaelli, G.,Fiocchi, A.,Riva, E. Growth pattern of breastfed and nonbreastfed infants with atopic dermatitis in the first year of life. Pediatrics. 2000;106(5):E73. | Independent variable
19 | Agostoni, C.,Marangoni, F.,Giovannini, M.,Galli, C.,Riva, E. Prolonged breast-feeding (six months or more) and milk fat content at six months are associated with higher developmental scores at one year of age within a breast-fed population. Adv Exp Med Biol. 2001;501:137-41. | Group size
20 | Agostoni, C.,Marangoni, F.,Lammardo, A. M.,Giovannini, M.,Riva, E.,Galli, C. Breastfeeding duration, milk fat composition and developmental indices at 1 year of life among breastfed infants. Prostaglandins Leukot Essent Fatty Acids. 2001;64(2):105-9. | Included for systematic reviews not completed
21 | Agostoni, C.,Riva, E.,Bellu, R.,Trojan, S.,Luotti, D.,Giovannini, M. Effects of diet on the lipid and fatty acid status of full-term infants at 4 months. J Am Coll Nutr. 1994;13(6):658-64. | Group size
22 | Agostoni, C.,Trojan, S.,Bellu, R.,Riva, E.,Giovannini, M. Neurodevelopmental quotient of healthy term infants at 4 months and feeding practice: the role of long-chain polyunsaturated fatty acids. Pediatr Res. 1995;38(2):262-6. | Included for systematic reviews not completed
23 | Agras, W. S.,Kraemer, H. C.,Berkowitz, R. I.,Hammer, L. D. Influence of early feeding style on adiposity at 6 years of age. J Pediatr. 1990;116(5):805-9. | Group size
24 | Agras, W. S.,Kraemer, H. C.,Berkowitz, R. I.,Korner, A. F.,Hammer, L. D. Does a vigorous feeding style influence early development of adiposity?. J Pediatr. 1987;110(5):799-804. | Independent variable
25 | Agre, F. The relationship of mode of infant feeding and location of care to frequency of infection. Am J Dis Child. 1985;139(8):809-11. | Dependent variable
26 | Ahn, C. H.,MacLean, W. C., Jr. Growth of the exclusively breast-fed infant. Am J Clin Nutr. 1980;33(2):183-92. | Study design, Independent variable
27 | Ahn, S. K.,Kam, S.,Chun, B. Y. Incidence of and factors for self-reported fragility fractures among middle-aged and elderly women in rural Korea: An 11-year follow-up study. Journal of Preventive Medicine and Public Health. 2014;47(6):289-297. | Age
28 | Ajetunmobi, O. M.,Whyte, B.,Chalmers, J.,Tappin, D. M.,Wolfson, L.,Fleming, M.,MacDonald, A.,Wood, R.,Stockton, D. L. Breastfeeding is associated with reduced childhood hospitalization: evidence from a Scottish Birth Cohort (1997-2009). J Pediatr. 2015;166(3):620-5 e4. | Independent variable
29 | Akeson, P. K.,Axelsson, I. E.,Raiha, N. C.,Warm, A.,Minoli, I.,Moro, G. Fat intake and metabolism in Swedish and Italian infants. Acta Paediatr. 2000;89(1):28-33. | Independent variable
30 | Akeson, P. M.,Axelsson, I. E.,Raiha, N. C. Growth and nutrient intake in three- to twelve-month-old infants fed human milk or formulas with varying protein concentrations. J Pediatr Gastroenterol Nutr. 1998;26(1):1-8. | Study design
31 | Akeson, P. M.,Axelsson, I. E.,Raiha, N. C.. Plasma lipids and apolipoproteins in breastfed and formula-fed Swedish infants. Acta Paediatr. 1999;88(1):1-6. | Dependent variable
32 | Akkus, Z.,Camdeviren, H.,Celik, F.,Gur, A.,Nas, K. Determination of osteoporosis risk factors using a mutiple logistic regression model in postmenopausal Turkish women. Saudi Medical Journal. 2005;26(9):1351-1359. | Age
33 | Al Mamun, A.,O’Callaghan, M. J.,Williams, G. M.,Najman, J. M.,Callaway, L.,McIntyre, H. D.. Breastfeeding is protective to diabetes risk in young adults: a longitudinal study. Acta Diabetol. 2015;52(5):837-44. | Dependent variable
34 | Al-Abbad, A. A.,Bella, H. Diarrhoea in the under-fives in a Saudi semiurban community. Tropical and Geographical Medicine. 1990;42(3):233-237. | Study design
35 | al-Ali, F. M.,Hossain, M. M.,Pugh, R. N. The associations between feeding modes and diarrhoea among urban children in a newly developed country. Public Health. 1997;111(4):239-43. | Independent variable
36 | Alaluusua, S.,Lukinmaa, P. L.,Koskimies, M.,Pirinen, S.,Holtta, P.,Kallio, M.,Holttinen, T.,Salmenpera, L. Developmental dental defects associated with long breast feeding. Eur J Oral Sci. 1996;104(5-6):493-7. | Group size
37 | Alaluusua, S.,Myllarniemi, S.,Kallio, M.,Salmenpera, L.,Tainio, V. M. Prevalence of caries and salivary levels of mutans streptococci in 5-year-old children in relation to duration of breast feeding. Scand J Dent Res. 1990;98(3):193-6. | Included for systematic reviews not completed
38 | Alam, S.,Ahmad, S. A.,Kumar, S. Dietary regimen for persistent diarrhea in infants under four months. Indian Pediatr. 2001;38(4):396-400. | Country
39 | Al-Atawi, M. S.,Al-Alwan, I. A.,Al-Mutair, A. N.,Tamim, H. M.,Al-Jurayyan, N. A. Epidemiology of nutritional rickets in children. Saudi J Kidney Dis Transpl. 2009;20(2):260-5. | Study design
40 | Albert, R. J.,Cantin, R. Y.,Cross, H. G.,Castaldi, C. R. Nursing caries in the Inuit children of the Keewatin. J Can Dent Assoc. 1988;54(10):751-8. | Study design
41 | al-Dashti, A. A.,Williams, S. A.,Curzon, M. E. Breast feeding, bottle feeding and dental caries in Kuwait, a country with low-fluoride levels in the water supply. Community Dent Health. 1995;12(1):42-7. | Study design
42 | Alderete, T. L.,Autran, C.,Brekke, B. E.,Knight, R.,Bode, L.,Goran, M. I.,Fields, D. A. Associations between human milk oligosaccharides and infant body composition in the first 6 mo of life. Am J Clin Nutr. 2015;102(6):1381-8. | Independent variable
43 | Alexander, D. A. Breastfeeding study needs to be viewed in context..‘Breastfeeding may increase the risk of asthma and allergies’ (Specialty News Bulletin, December 2002). RN. 2003;66(4):10-10 1p. | Study design
44 | Alexander, E. S.,Martin, L. J.,Collins, M. H.,Kottyan, L. C.,Sucharew, H.,He, H.,Mukkada, V. A.,Succop, P. A.,Abonia, J. P.,Foote, H.,Eby, M. D.,Grotjan, T. M.,Greenler, A. J.,Dellon, E. S.,Demain, J. G.,Furuta, G. T.,Gurian, L. E.,Harley, J. B.,Hopp, R. J.,Kagalwalla, A.,Kaul, A.,Nadeau, K. C.,Noel, R. J.,Putnam, P. E.,von Tiehl, K. F.,Rothenberg, M. E. Twin and family studies reveal strong environmental and weaker genetic cues explaining heritability of eosinophilic esophagitis. J Allergy Clin Immunol. 2014;134(5):1084-1092 e1. | Study design, Dependent variable
45 | Alexy, U.,Kersting, M.,Sichert-Hellert, W.,Manz, F.,Schoch, G. Energy intake and growth of 3- to 36-month-old German infants and children. Ann Nutr Metab. 1998;42(2):68-74. | Study design
46 | Al-Farsi, Y. M.,Al-Sharbati, M. M.,Waly, M. I.,Al-Farsi, O. A.,Al-Shafaee, M. A.,Al-Khaduri, M. M.,Trivedi, M. S.,Deth, R. C. Effect of suboptimal breast-feeding on occurrence of autism: a case-control study. Nutrition. 2012;28(7-8):e27-32. | Study design
47 | Alho, O. P.,Koivu, M.,Sorri, M.,Rantakallio, P. Risk factors for recurrent acute otitis media and respiratory infection in infancy. Int J Pediatr Otorhinolaryngol. 1990;19(2):151-61. | Included for systematic reviews not completed
48 | Alho, O. P.,Laara, E.,Oja, H. Public health impact of various risk factors for acute otitis media in northern Finland. Am J Epidemiol. 1996;143(11):1149-56. | Included for systematic reviews not completed
49 | Alho, O. P.,Laara,Oja, H. How should relative risk estimates for acute otitis media in children aged less than 2 years be perceived?. J Clin Epidemiol. 1996;49(1):9-14. | Independent variable
50 | Ali, M. B.,Ghenghesh, K. S.,Aissa, R. B.,Abuhelfaia, A.,Dufani, M. Etiology of childhood diarrhea in Zliten, Libya. Saudi Med J. 2005;26(11):1759-65. | Study design, Health status
51 | Al-Jassir, M. S.,El-Bashir, B. M.,Moizuddin, S. K. Surveillance of infant feeding practices in Riyadh city. Ann Saudi Med. 2004;24(2):136-40. | Study design, Dependent variable
52 | Allen, J.,Hector, D. Benefits of breastfeeding. New South Wales public health bulletin. 2005;16(3-4):42-46. | Study design
53 | Allen, N. B.,Lewinsohn, P. M.,Seeley, J. R. Prenatal and perinatal influences on risk for psychopathology in childhood and adolescence. Dev Psychopathol. 1998;10(3):513-29. | Study design
54 | Allergy in your baby. Aust Fam Physician. 1986;15(2):176, 178. | Study design
55 | Alliet, P.,Scholtens, P.,Raes, M.,Hensen, K.,Jongen, H.,Rummens, J. L.,Boehm, G.,Vandenplas, Y. Effect of prebiotic galacto-oligosaccharide, long-chain fructo-oligosaccharide infant formula on serum cholesterol and triacylglycerol levels. Nutrition. 2007;23(10):719-23. | Group size
56 | Alm, B.,Aberg, N.,Erdes, L.,Mollborg, P.,Pettersson, R.,Norvenius, S. G.,Goksor, E.,Wennergren, G. Early introduction of fish decreases the risk of eczema in infants. Arch Dis Child. 2009;94(1):11-5. | Independent variable
57 | Alm, B.,Erdes, L.,Mollborg, P.,Pettersson, R.,Norvenius, S. G.,Aberg, N.,Wennergren, G. Neonatal antibiotic treatment is a risk factor for early wheezing. Pediatrics. 2008;121(4):697-702. | Dependent variable
58 | Alm, B.,Norvenius, S. G.,Wennergren, G.,Lagercrantz, H.,Helweg-Larsen, K.,Irgens, L. M. Living conditions in early infancy in Denmark, Norway and Sweden 1992-95: results from the Nordic Epidemiological SIDS study. Acta Paediatr. 2000;89(2):208-14. | Study design
59 | Alm, B.,Wennergren, G.,Norvenius, S. G.,Skjaerven, R.,Lagercrantz, H.,Helweg-Larsen, K.,Irgens, L. M. Breast feeding and the sudden infant death syndrome in Scandinavia, 1992-95. Arch Dis Child. 2002;86(6):400-2. | Included for systematic reviews not completed
60 | Almeida, R. M.,De Marins, V. M.,Valle, J. Breastfeeding, socio-economic conditions and nutritional status of children younger than 12 months in Brazil. Ann Trop Paediatr. 1999;19(3):257-62. | Study design
61 | Almquist-Tangen, G.,Dahlgren, J.,Roswall, J.,Bergman, S.,Alm, B. Milk cereal drink increases BMI risk at 12 and 18 months, but formula does not. Acta Paediatr. 2013;102(12):1174-9. | Independent variable
62 | Al-Mustafa, Z. H.,Al-Madan, M.,Al-Majid, H. J.,Al-Muslem, S.,Al-Ateeq, S.,Al-Ali, A. K. Vitamin D deficiency and rickets in the Eastern Province of Saudi Arabia. Ann Trop Paediatr. 2007;27(1):63-7. | Included for systematic reviews not completed
63 | Alper, C. M.,Winther, B.,Hendley, J. O.,Doyle, W. J. Cytokine polymorphisms predict the frequency of otitis media as a complication of rhinovirus and RSV infections in children. Eur Arch Otorhinolaryngol. 2009;266(2):199-205. | Included for systematic reviews not completed
64 | Alper, C. M.,Winther, B.,Mandel, E. M.,Hendley, J. O.,Doyle, W. J. Rate of concurrent otitis media in upper respiratory tract infections with specific viruses. Arch Otolaryngol Head Neck Surg. 2009;135(1):17-21. | Study design
65 | Al-Qaoud, N.,Prakash, P. Breastfeeding and obesity among Kuwaiti preschool children. Medical Principles and Practice. 2009;18(2):111-117. | Study design
66 | Al-Qaoud, N.,Prakash, P. ‘Can breastfeeding and its duration determine the overweight status of Kuwaiti children at the age of 3-6 years?’. Eur J Clin Nutr. 2009;63(8):1041-3. | Study design
67 | Al-Shehri, M. A.,Sadeq, A.,Quli, K. Bronchiolitis in Abha, Southwest Saudi Arabia: viral etiology and predictors for hospital admission. West Afr J Med. 2005;24(4):299-304. | Health status
68 | Al-Shehri, S. S.,Knox, C. L.,Liley, H. G.,Cowley, D. M.,Wright, J. R.,Henman, M. G.,Hewavitharana, A. K.,Charles, B. G.,Shaw, P. N.,Sweeney, E. L.,Duley, J. A. Breastmilk-Saliva Interactions Boost Innate Immunity by Regulating the Oral Microbiome in Early Infancy. PLoS One. 2015;10(9):e0135047. | Independent variable, Dependent variable
69 | Althaus BW. Growth patterns of Hispanic and Caucasian children: Texas Woman’s University; 1999. | Study design
70 | Altinkaynak, S.,Selimoglu, M. A.,Turgut, A.,Kilicaslan, B.,Ertekin, V. Breast-feeding duration and childhood acute leukemia and lymphomas in a sample of Turkish children. Journal of Pediatric Gastroenterology and Nutrition. 2006;42(5):568-572. | Independent variable
71 | Altucher, K.,Rasmussen, K. M.,Barden, E. M.,Habicht, J. P. Predictors of improvement in hemoglobin concentration among toddlers enrolled in the Massachusetts WIC Program. J Am Diet Assoc. 2005;105(5):709-15. | Study design
72 | Alvarado, B. E.,Zunzunegui, M. V.,Delisle, H.,Osorno, J. Growth trajectories are influenced by breast-feeding and infant health in an afro-colombian community. J Nutr. 2005;135(9):2171-8. | Independent variable
73 | Alvarado, R.,Zepeda, A.,Rivero, S.,Rico, N.,Lopez, S.,Diaz, S. Integrated maternal and infant health care in the postpartum period in a poor neighborhood in Santiago, Chile. Stud Fam Plann. 1999;30(2):133-41. | Included for systematic reviews not completed
74 | Alves, J. G.,Figueira, F.,Nacul, L. C. Hospital induced malnutrition in infants: prevention by relactation. Indian Pediatr. 1999;36(5):484-7. | Health status
75 | Amador, M.,Hermelo, M. P.,Canetti, J. E.,Consuegra, E. Adolescent mothers: do they breast-feed less?. Acta Paediatr Hung. 1992;32(3):269-85. | Study design
76 | Amador-Licona, N.,Martinez-Cordero, C.,Guizar-Mendoza, J. M.,Malacara, J. M.,Hernandez, J.,Alcala, J. F. Catch-up growth in infants born small for gestational age--a longitudinal study. J Pediatr Endocrinol Metab. 2007;20(3):379-86. | Study design
77 | Amaratunge, A.,Ekanayake, S. L. Rampant caries in Sri Lankan children. A pilot study. Odontostomatol Trop. 1984;7(3):133-8. | Group size
78 | American Academy of Pediatrics Committee on Nutrition: Follow-up or weaning formulas. Pediatrics. 1989;83(6):1067. | Study design
79 | Amigo, H.,Bustos, P.,Leone, C.,Radrigán, M. E. Community and international nutrition: Growth deficits in Chilean school children. Journal of Nutrition. 2001;131(2):251-254. | Independent variable
80 | Ananthakrishnan, S.,Bhat, B. V.,Puri, R. K.,Srinivasan, S. Loose stools in the early neonatal period. Indian Pediatr. 1992;29(8):1005-9. | Country
81 | Ancona, J.,Shaker, C. S.,Puhek, J.,Garland, J. S. Improving outcomes through a developmental approach to nipple feeding. J Nurs Care Qual. 1998;12(5):1-4. | Study design
82 | Andersen, G. E. Changes in plasma lipoproteins from first day to third week of human life. Prog Clin Biol Res. 1985;188:87-91. | Study design
83 | Andersen, L. B.,Pipper, C. B.,Trolle, E.,Bro, R.,Larnkjaer, A.,Carlsen, E. M.,Molgaard, C.,Michaelsen, K. F. Maternal obesity and offspring dietary patterns at 9 months of age. Eur J Clin Nutr. 2015;69(6):668-75. | Independent variable
84 | Anderson, G. H.,Morson-Pasut, L. A.,Bryan, H.,Cleghorn, G.,Tanaka, P.,Yeung, D.,Zimmerman, B. Age of introduction of cow’s milk to infants. J Pediatr Gastroenterol Nutr. 1985;4(5):692-8. | Study design
85 | Anderson, J. E.,Marks, J. S.,Park, T. K. Breast-feeding, birth interval, and infant health. Pediatrics. 1984;74(4 Pt 2):695-701. | Study design
86 | Anderson, J.,Hayes, D.,Chock, L. Characteristics of overweight and obesity at age two and the association with breastfeeding in Hawai’i Women, Infants, and Children (WIC) participants. Matern Child Health J. 2014;18(10):2323-31. | Included for systematic reviews not completed
87 | Anderson, K. The sweet and sour of pediatric caries. CDS Rev. 2001;94(7):16-9. | Study design
88 | Anderson, L. J.,Parker, R. A.,Strikas, R. A.,Farrar, J. A.,Gangarosa, E. J.,Keyserling, H. L.,Sikes, R. K. Day-care center attendance and hospitalization for lower respiratory tract illness. Pediatrics. 1988;82(3):300-308. | Included for systematic reviews not completed
89 | Anderson, P. O.,Valdes, V. Variation of milk intake over time: clinical and pharmacokinetic implications. Breastfeed Med. 2015;10(3):142-4. | Study design, Dependent variable
90 | Andreev, A.,Arjas, E. Acute middle ear infection in small children: a Bayesian analysis using multiple time scales. Lifetime Data Anal. 1998;4(2):121-37. | Study design
91 | Andres, A.,Casey, P. H.,Cleves, M. A.,Badger, T. M. Body fat and bone mineral content of infants fed breast milk, cow’s milk formula, or soy formula during the first year of life. J Pediatr. 2013;163(1):49-54. | Independent variable
92 | Andres, A.,Cleves, M. A.,Bellando, J. B.,Pivik, R. T.,Casey, P. H.,Badger, T. M. Developmental status of 1-year-old infants fed breast milk, cow’s milk formula, or soy formula. Pediatrics. 2012;129(6):1134-40. | Independent variable
93 | Anfield, L. Nutrition in the first year. Midwife Health Visit Community Nurse. 1985;21(5):161-4. | Study design
94 | Angelsen, N. K.,Vik, T.,Jacobsen, G.,Bakketeig, L. S. Breast feeding and cognitive development at age 1 and 5 years. Arch Dis Child. 2001;85(3):183-8. | Included for systematic reviews not completed
95 | Angulo, N.,de Szarvas, S. B.,Guevara, H.,Mathison, Y.,González, D.,Hernández, A. Lifestyle of a group of obese children located in Valencia. Salus. 2014;18(1):25-31. | Language
96 | Anholm, P. C. Breastfeeding: a preventive approach to health care in infancy. Issues Compr Pediatr Nurs. 1986;9(1):1-10. | Study design
97 | Aniansson, G.,Alm, B.,Andersson, B.,Hakansson, A.,Larsson, P.,Nylen, O.,Peterson, H.,Rigner, P.,Svanborg, M.,Sabharwal, H.,et al.,. A prospective cohort study on breast-feeding and otitis media in Swedish infants. Pediatr Infect Dis J. 1994;13(3):183-8. | Included for systematic reviews not completed
98 | Annamalay, A. A.,Khoo, S. K.,Jacoby, P.,Bizzintino, J.,Zhang, G.,Chidlow, G.,Lee, W. M.,Moore, H. C.,Harnett, G. B.,Smith, D. W.,Gern, J. E.,LeSouef, P. N.,Laing, I. A.,Lehmann, D. Prevalence of and risk factors for human rhinovirus infection in healthy aboriginal and non-aboriginal Western Australian children. Pediatr Infect Dis J. 2012;31(7):673-9. | Dependent variable
99 | Ansari-Moghaddam, A.,Sadeghi-Bojd, S.,Imani, M.,Movahedinia, S.,Pourrashidi, A.,Mohammadi, M. A multivariate analysis of factors associated with infant mortality in South-East of Iran. J Pak Med Assoc. 2014;64(10):1123-6. | Included for systematic reviews not completed
100 | Apostolopoulos, K.,Xenelis, J.,Tzagaroulakis, A.,Kandiloros, D.,Yiotakis, J.,Papafragou, K. The point prevalence of otitis media with effusion among school children in Greece. International Journal of Pediatric Otorhinolaryngology. 1998;44(3):207-214. | Study design
101 | Apps, J. R.,Beattie, R. M. Cow’s milk allergy in children. BMJ. 2009;339:b2275. | Study design
102 | Araujo, C. L.,Victora, C. G.,Hallal, P. C.,Gigante, D. P. Breastfeeding and overweight in childhood: evidence from the Pelotas 1993 birth cohort study. Int J Obes (Lond). 2006;30(3):500-6. | Included for systematic reviews not completed
103 | Araujo, D. S.,Marquezin, M. C.,Barbosa, T. S.,Gaviao, M. B.,Castelo, P. M. Evaluation of masticatory parameters in overweight and obese children. Eur J Orthod. 2015. | Study design
104 | Arica, S.,Arica, V.,Dag, H.,Kaya, A.,Hatipoglu, S.,Fenercioglu, A.,Karatekin, G. Serum zinc levels in children of 0-24 months diagnosed with pneumonia admitted to our clinic. International Journal of Clinical and Experimental Medicine. 2011;4(3):227-233. | Independent variable, Health status
105 | Arimond, M.,Daelmans, B.,Dewey, K. Indicators for feeding practices in children. Lancet. 2008;371(9612):541-2. | Study design
106 | Aris, I. M.,Soh, S. E.,Tint, M. T.,Saw, S. M.,Rajadurai, V. S.,Godfrey, K. M.,Gluckman, P. D.,Yap, F.,Chong, Y. S.,Lee, Y. S. Associations of infant milk feed type on early postnatal growth of offspring exposed and unexposed to gestational diabetes in utero. Eur J Nutr. 2015. | Included for systematic reviews not completed
107 | Arlette, J. P. Zinc deficiency in children. Int J Dermatol. 1982;21(8):447-8. | Study design
108 | Armstrong, J.,Reilly, J. J. Breastfeeding and lowering the risk of childhood obesity. Lancet. 2002;359(9322):2003-4. | Included for systematic reviews not completed
109 | Arnon, S. S.,Damus, K.,Thompson, B.,Midura, T. F.,Chin, J. Protective role of human milk against sudden death from infant botulism. J Pediatr. 1982;100(4):568-73. | Group size
110 | Arora, N. K.,Bhan, M. K. Nutritional management of acute diarrhea. Indian J Pediatr. 1991;58(6):763-7. | Study design, Country
111 | Arshad, S. H.,Bateman, B.,Matthews, S. M. Primary prevention of asthma and atopy during childhood by allergen avoidance in infancy: a randomised controlled study. Thorax. 2003;58(6):489-93. | Independent variable
112 | Arshad, S. H.,Bateman, B.,Sadeghnejad, A.,Gant, C.,Matthews, S. M. Prevention of allergic disease during childhood by allergen avoidance: the Isle of Wight prevention study. J Allergy Clin Immunol. 2007;119(2):307-13. | Independent variable
113 | Arton M. Breast feeding--a life-saver in the Third World. Midwives Chron. 1985;98:200-1. | Study design
114 | Aryayev, N.,Kukushkin, V. The perinatal risk factors of sudden infant death syndrome. Perinatology. 2002;4(3):125-133. | No full text
115 | Aryayev, N.,Kukushkin, V.,Nepomyashcha, V. The significance of ante- and perinatal periods for formation of risk of sudden infant death syndrome. Ginekologia polska. 2001;72(12):931-939. | Included for systematic reviews not completed
116 | Asaka, A.,Imaizumi, Y.,Inouye, E. Analysis of multiple births in Japan. V. Effects of gestational age, maternal age and other factors on growth rate of weight in twins. Jinrui Idengaku Zasshi. 1981;26(2):83-90. | Study design
117 | Ascher, H.,Krantz, I.,Rydberg, L.,Nordin, P.,Kristiansson, B. Influence of infant feeding and gluten intake on coeliac disease. Arch Dis Child. 1997;76(2):113-7. | Group size
118 | Asha Bai, P. V.,Leela, M.,Subramaniam, V. R. Adequacy of breast milk for optimal growth of infants. Trop Geogr Med. 1980;32(2):158-62. | Country
119 | Ashraf, A. P.,Eason, N. B.,Kabagambe, E. K.,Haritha, J.,Meleth, S.,McCormick, K. L. Dietary iron intake in the first 4 months of infancy and the development of type 1 diabetes: A pilot study. Diabetology and Metabolic Syndrome. 2010;2(1). | Study design
120 | Askie, L.,Martin, A.,Espinoza, D.,Campbell, K.,Daniels, L. A.,Hesketh, K.,Margarey, A.,Rissel, C.,Taylor, B.,Taylor, R.,Wen, L. M.,Baur, L. A. What does the EPOCH (early prevention of obesity in childhood) prospective meta-analysis tell us about early life obesity prevention?. Obesity research & clinical practice. 2014;8:3-4. | Study design
121 | Assuncao, M. L.,Ferreira, H. S.,Coutinho, S. B.,Santos, L. M.,Horta, B. L. Protective effect of breastfeeding against overweight can be detected as early as the second year of life: a study of children from one of the most socially-deprived areas of Brazil. J Health Popul Nutr. 2015;33(1):85-91. | Study design, Independent variable
122 | Astarita, C.,Harris, R. I.,de Fusco, R.,Franzese, A.,Biscardi, D.,Mazzacca, F. R.,Altucci, P. An epidemiological study of atopy in children. Clin Allergy. 1988;18(4):341-50. | Study design
123 | Atkins, L. A.,McNaughton, S. A.,Campbell, K. J.,Szymlek-Gay, E. A. Iron intakes of Australian infants and toddlers: findings from the Melbourne Infant Feeding, Activity and Nutrition Trial (InFANT) Program. Br J Nutr. 2015:1-9. | Dependent variable
124 | Atladottir, H.,Thorsdottir, I. Energy intake and growth of infants in Iceland-a population with high frequency of breast-feeding and high birth weight. Eur J Clin Nutr. 2000;54(9):695-701. | Independent variable
125 | Auerbach, K. G.,Renfrew, M. J.,Minchin, M. Infant feeding comparisons: a hazard to infant health?. J Hum Lact. 1991;7(2):63-8. | Study design
126 | Auestad, N.,Halter, R.,Hall, R. T.,Blatter, M.,Bogle, M. L.,Burks, W.,Erickson, J. R.,Fitzgerald, K. M.,Dobson, V.,Innis, S. M.,Singer, L. T.,Montalto, M. B.,Jacobs, J. R.,Qiu, W.,Bornstein, M. H. Growth and development in term infants fed long-chain polyunsaturated fatty acids: a double-masked, randomized, parallel, prospective, multivariate study. Pediatrics. 2001;108(2):372-81. | Independent variable
127 | Auestad, N.,Montalto, M. B.,Hall, R. T.,Fitzgerald, K. M.,Wheeler, R. E.,Connor, W. E.,Neuringer, M.,Connor, S. L.,Taylor, J. A.,Hartmann, E. E. Visual acuity, erythrocyte fatty acid composition, and growth in term infants fed formulas with long chain polyunsaturated fatty acids for one year. Ross Pediatric Lipid Study. Pediatr Res. 1997;41(1):1-10. | Independent variable
128 | Auestad, N.,Scott, D. T.,Janowsky, J. S.,Jacobsen, C.,Carroll, R. E.,Montalto, M. B.,Halter, R.,Qiu, W.,Jacobs, J. R.,Connor, W. E.,Connor, S. L.,Taylor, J. A.,Neuringer, M.,Fitzgerald, K. M.,Hall, R. T. Visual, cognitive, and language assessments at 39 months: a follow-up study of children fed formulas containing long-chain polyunsaturated fatty acids to 1 year of age. Pediatrics. 2003;112(3 Pt 1):e177-83. | Independent variable
129 | Avoa, A.,Fischer, P. R. The influence of perinatal instruction about breast-feeding on neonatal weight loss. Pediatrics. 1990;86(2):313-5. | Country
130 | Awasthi, S.,Misra, P. K.,Malik, G. K. Adequacy of breast milk. Indian Pediatr. 1987;24(10):873-7. | Country
131 | Axelsson, I. E.,Ivarsson, S. A.,Raiha, N. C. Protein intake in early infancy: effects on plasma amino acid concentrations, insulin metabolism, and growth. Pediatr Res. 1989;26(6):614-7. | Group size
132 | Axelsson, I.,Borulf, S.,Righard, L.,Raiha, N. Protein and energy intake during weaning: I. Effects on growth. Acta Paediatr Scand. 1987;76(2):321-7. | Group size
133 | Ayatollahi, S. M.,Sharafi, Z.,Haem, E. Child Weight Growth Chart and Its Associated Factors in Birth Cohort of Maku Using a Growth Curve Model and LMS Method. Glob J Health Sci. 2015;7(6):44045. | Group size
134 | Aydemir, G.,Ozkurt, F. E. Otitis media with effusion in primary schools in Princes’ Islands, Istanbul: Prevalence and risk factors. Journal of International Medical Research. 2011;39(3):866-872. | Study design
135 | Ayer, J. G.,Belousova, E.,Harmer, J. A.,David, C.,Marks, G. B.,Celermajer, D. S. Maternal cigarette smoking is associated with reduced high-density lipoprotein cholesterol in healthy 8-year-old children. Eur Heart J. 2011;32(19):2446-53. | Independent variable
136 | Azizi, B. H.,Zulkifli, H. I.,Kasim, M. S. Protective and risk factors for acute respiratory infections in hospitalized urban Malaysian children: a case control study. Southeast Asian J Trop Med Public Health. 1995;26(2):280-5. | Study design
137 | Babeely, K.,Kaste, L. M.,Husain, J.,Behbehani, J.,al-Za’abi, F.,Maher, T. C.,Tavares, M.,Soparkar, P.,DePaola, P. Severity of nursing-bottle syndrome and feeding patterns in Kuwait. Community Dent Oral Epidemiol. 1989;17(5):237-9. | Study design, Independent variable
138 | Backon, J. Prolonged breast feeding as a prophylaxis for recurrent otitis media: relevance of prostaglandins. Med Hypotheses. 1984;13(2):161. | Study design
139 | Bacopoulou, F.,Veltsista, A.,Vassi, I.,Gika, A.,Lekea, V.,Priftis, K.,Bakoula, C. Can we be optimistic about asthma in childhood? A Greek cohort study. J Asthma. 2009;46(2):171-4. | Independent variable
140 | Badger, T. Effects of soy infant formula on growth and development in the first year of life. Food Nutr Bull. 2013;34(2):252-3. | Study design, Independent variable
141 | Badger, Thomas M. STUDY SUGGESTS SOY FORMULA MAY BE GOOD CHOICE FOR SOME INFANTS. JAAPA: Journal of the American Academy of Physician Assistants (Lippincott Williams & Wilkins). 2014;27(5):1-3 3p. | Study design
142 | Bagnoli, F.,Casucci, M.,Toti, S.,Cecchi, S.,Iurato, C.,Coriolani, G.,Tiezzi, M.,Vispi, L. Is vitamin D supplementation necessary in healthy full-term breastfed infants? A follow-up study of bone mineralization in healthy full-term infants with and without supplemental vitamin D. Minerva Pediatr. 2013;65(3):253-60. | Group size
143 | Baheiraei, A.,Ardsetani, N.,Ghazizadeh, Sh. Effects of progestogen-only contraceptives on breast-feeding and infant growth. International Journal of Gynecology and Obstetrics. 2001;74(2):203-205. | Independent variable
144 | Bahl, R.,Frost, C.,Kirkwood, B. R.,Edmond, K.,Martines, J.,Bhandari, N.,Arthur, P. Infant feeding patterns and risks of death and hospitalization in the first half of infancy: multicentre cohort study. Bull World Health Organ. 2005;83(6):418-26. | Included for systematic reviews not completed
145 | Bai, K. I.,Sastry, V. N.,Reddy, C. C. A comparative study of feeding pattern of infants in rural and urban areas. Indian J Pediatr. 1981;48(392):277-80. | Country
146 | Bailey W. Malnutrition among babies born to adolescent mothers. West Indian Med J. 1981;30:72-6. | Dependent variable, Health status
147 | Bailey, P.,Tsui, A. O.,Janowitz, B.,Dominik, R.,Araujo, L. A study of infant mortality and causes of death in a rural north-east Brazilian community. J Biosoc Sci. 1990;22(3):349-63. | Included for systematic reviews not completed
148 | Bailey, W. Clinical undernutrition in the Kingston/St Andrew metropolitan area: 1967-1976. Soc Sci Med D. 1981;15(4):471-7. | Study design, Dependent variable
149 | Bainbridge, J. Breastfed babies less likely to become overweight children. British Journal of Midwifery. 2009;17(6):393-393 1p. | Study design
150 | Bainbridge, J. Higher IQs for breastfed babies. British Journal of Midwifery. 2008;16(6):394-394 1p. | Study design
151 | Baird, J.,Poole, J.,Robinson, S.,Marriott, L.,Godfrey, K.,Cooper, C.,Inskip, H.,Law, C. Milk feeding and dietary patterns predict weight and fat gains in infancy. Paediatr Perinat Epidemiol. 2008;22(6):575-86. | Included for systematic reviews not completed
152 | Baker, D.,Taylor, H.,Henderson, J. Inequality in infant morbidity: Causes and consequences in England in the 1990s. Journal of Epidemiology and Community Health. 1998;52(7):451-458. | Included for systematic reviews not completed
153 | Baker, D.,Taylor, H.,Henderson, J.. Inequality in infant morbidity: causes and consequences in England in the 1990s. ALSPAC Study Team. Avon Longitudinal Study of Pregnancy and Childhood. J Epidemiol Community Health. 1998;52(7):451-8. | Duplicate
154 | Baker, J. L.,Michaelsen, K. F.,Rasmussen, K. M.,Sorensen, T. I. Maternal prepregnant body mass index, duration of breastfeeding, and timing of complementary food introduction are associated with infant weight gain. Am J Clin Nutr. 2004;80(6):1579-88. | Included for systematic reviews not completed
155 | Baker, R. J.,Hertz-Picciotto, I.,Dostal, M.,Keller, J. A.,Nozicka, J.,Kotesovec, F.,Dejmek, J.,Loomis, D.,Sram, R. J. Coal home heating and environmental tobacco smoke in relation to lower respiratory illness in Czech children, from birth to 3 years of age. Environ Health Perspect. 2006;114(7):1126-32. | Included for systematic reviews not completed
156 | Balaban, G.,Motta, M. E.,Silva, G. A. Early weaning and other potential risk factors for overweight among preschool children. Clinics (Sao Paulo). 2010;65(2):181-7. | Study design
157 | Ball, T. M.,Wright, A. L. Health care costs of formula-feeding in the first year of life. Pediatrics. 1999;103(4 Pt 2):870-6. | Included for systematic reviews not completed
158 | Bammann, K.,Peplies, J.,De Henauw, S.,Hunsberger, M.,Molnar, D.,Moreno, L. A.,Tornaritis, M.,Veidebaum, T.,Ahrens, W.,Siani, A. Early life course risk factors for childhood obesity: the IDEFICS case-control study. PLoS One. 2014;9(2):e86914. | Included for systematic reviews not completed
159 | Bandara, T.,Hettiarachchi, M.,Liyanage, C.,Amarasena, S. Current infant feeding practices and impact on growth in babies during the second half of infancy. J Hum Nutr Diet. 2015;28(4):366-74. | Study design
160 | Bandoli, G.,von Ehrenstein, O. S.,Flores, M. E.,Ritz, B. Breastfeeding and Asthmatic Symptoms in The Offspring of Latinas: The Role of Maternal Nativity. J Immigr Minor Health. 2015;17(6):1739-45. | Study design
161 | Bandurska-Stankiewicz, E.,Rutkowska, J. Environmental risk factors for type 1 diabetes in the north of Poland. Diabetologia Doswiadczalna i Kliniczna. 2008;8(2):81-84. | Study design
162 | Banerji, A.,Greenberg, D.,White, L. F.,Macdonald, W. A.,Saxton, A.,Thomas, E.,Sage, D.,Mamdani, M.,Lanctot, K. L.,Mahony, J. B.,Dingle, M.,Roberts, A. Risk factors and viruses associated with hospitalization due to lower respiratory tract infections in Canadian Inuit children : a case-control study. Pediatr Infect Dis J. 2009;28(8):697-701. | Included for systematic reviews not completed
163 | Bankel, M.,Robertson, A.,Kohler, B. Carious lesions and caries risk predictors in a group of Swedish children 2 to 3 years of age. One year observation. Eur J Paediatr Dent. 2011;12(4):215-9. | Study design
164 | Baranowski, T.,Bryan, G. T.,Harrison, J. A.,Rassin, D. K.,Greaves, K. A.,Baranowski, J. H. Height, infant-feeding practices and cardiovascular functioning among 3 or 4 year old children in three ethnic groups. J Clin Epidemiol. 1992;45(5):513-8. | Study design
165 | Baranowski, T.,Bryan, G. T.,Rassin, D. K.,Harrison, J. A.,Henske, J. C. Ethnicity, infant-feeding practices, and childhood adiposity. J Dev Behav Pediatr. 1990;11(5):234-9. | Study design
166 | Barge, K. Breast-feeding doesn’t contribute to dental caries. J Dent Hyg. 2007;81(4):69. | Study design
167 | Barness LA. Impact of breast feeding--obviating problems. J Fla Med Assoc. 1983;70:831-2. | Study design
168 | Barreto, B. A.,Sole, D. Prevalence of asthma and associated factors in adolescents living in Belem (Amazon region), Para, Brazil. Allergol Immunopathol (Madr). 2014;42(5):427-32. | Study design
169 | Barros, F. C.,Rossello, J. L.,Matijasevich, A.,Dumith, S. C.,Barros, A. J.,dos Santos, I. S.,Mota, D.,Victora, C. G. Gestational age at birth and morbidity, mortality, and growth in the first 4 years of life: findings from three birth cohorts in Southern Brazil. BMC Pediatr. 2012;12:169. | Independent variable
170 | Barros, F. C.,Semer, T. C.,Tonioli Filho, S.,Tomasi, E.,Victora, C. G. The impact of lactation centres on breastfeeding patterns, morbidity and growth: a birth cohort study. Acta Paediatr. 1995;84(11):1221-6. | Included for systematic reviews not completed
171 | Barros, F. C.,Victora, C. G.,Morris, S. S.,Halpern, R.,Horta, B. L.,Tomasi, E. Breast feeding, pacifier use and infant development at 12 months of age: a birth cohort study in Brazil. Paediatr Perinat Epidemiol. 1997;11(4):441-50. | Included for systematic reviews not completed
172 | Barros, F. C.,Victora, C. G.,Vaughan, J. P.,Tomasi, E.,Horta, B. L.,Cesar, J. A.,Menezes, M. B.,Halpern, R.,Post, C. L.,del Mar Garcia, M. The epidemiological transition in maternal and child health in a Brazilian city, 1982-93: a comparison of two population-based cohorts. Paediatr Perinat Epidemiol. 2001;15(1):4-11. | Dependent variable
173 | Barroso, C. S.,Roncancio, A.,Hinojosa, M. B.,Reifsnider, E. The association between early childhood overweight and maternal factors. Child Obes. 2012;8(5):449-54. | Study design
174 | Barsam, F. J.,Borges, G. S.,Severino, A. B.,de Mello, L. M.,da Silva, A. S.,Nunes, A. A. Factors associated with community-acquired pneumonia in hospitalised children and adolescents aged 6 months to 13 years old. Eur J Pediatr. 2013;172(4):493-9. | Included for systematic reviews not completed
175 | Bartels, M.,van Beijsterveldt, C. E.,Boomsma, D. I. Breastfeeding, maternal education and cognitive function: a prospective study in twins. Behav Genet. 2009;39(6):616-22. | Included for systematic reviews not completed
176 | Bartok, C. J. Babies fed breastmilk by breast versus by bottle: a pilot study evaluating early growth patterns. Breastfeed Med. 2011;6(3):117-24. | Group size
177 | Barton, S. J.,Howard, P. K.,Rayens, M. K. The effects of infant feeding decisions on infant growth. J Spec Pediatr Nurs. 2002;7(2):64-70. | Group size
178 | Basheer, R. Breast is best. Nurs J India. 1988;79(7):180, 190. | Study design
179 | Bassal, R.,Reisfeld, A.,Nissan, I.,Agmon, V.,Taran, D.,Schemberg, B.,Cohen, D.,Shohat, T. Risk factors for sporadic infection with Salmonella Infantis: a matched case-control study. Epidemiol Infect. 2014;142(4):820-5. | Dependent variable
180 | Batstra, L.,Neeleman, J.,Hadders-Algra, M. Can breast feeding modify the adverse effects of smoking during pregnancy on the child’s cognitive development?. J Epidemiol Community Health. 2003;57(6):403-4. | Study design
181 | Bauer, G.,Ewald, L. S.,Hoffman, J.,Dubanoski, R. Breastfeeding and cognitive development of three-year-old children. Psychol Rep. 1991;68(3 Pt 2):1218. | Study design
182 | Baumgartner, C. Psychomotor and social development of breast-fed and bottle-fed babies during their first year of life. Acta Paediatr Hung. 1984;25(4):409-17. | Group size
183 | Baxter-Jones, A. D.,Cardy, A. H.,Helms, P. J.,Phillips, D. O.,Smith, W. C. Influence of socioeconomic conditions on growth in infancy: the 1921 Aberdeen birth cohort. Arch Dis Child. 1999;81(1):5-9. | Included for systematic reviews not completed
184 | Bayley, T. M.,Alasmi, M.,Thorkelson, T.,Jones, P. J.,Corcoran, J.,Krug-Wispe, S.,Tsang, R. C. Longer term effects of early dietary cholesterol level on synthesis and circulating cholesterol concentrations in human infants. Metabolism. 2002;51(1):25-33. | Group size
185 | Bayley, T. M.,Alasmi, M.,Thorkelson, T.,Krug-Wispe, S.,Jones, P. J.,Bulani, J. L.,Tsang, R. C. Influence of formula versus breast milk on cholesterol synthesis rates in four-month-old infants. Pediatr Res. 1998;44(1):60-7. | Group size
186 | Baylis, J. M.,Leeds, A. R.,Challacombe, D. N. Persistent nausea and food aversions in pregnancy. A possible association with cow’s milk allergy in infants. Clin Allergy. 1983;13(3):263-9. | Group size
187 | Bayraktar, S.,Bayraktar, S. T.,Selcuk, N.,Emiroglu, H.,Elevli, M. Lipid and lipoprotein profile of breast fed, formula fed or mixed-fed 0-6-month-old babies. International Pediatrics. 2006;21(2):84-90. | Study design
188 | Beath, K. J. Infant growth modelling using a shape invariant model with random effects. Stat Med. 2007;26(12):2547-64. | Included for systematic reviews not completed
189 | Beauchamp, J. N.,Gaboury, I.,Ni, A.,Boland, M. P.,Mac, K. D. R. Solid-food introduction in infants diagnosed as having a cow’s-milk protein-induced enterocolitis. Journal of Pediatric Gastroenterology and Nutrition. 2011;52(5):639-643. | Independent variable, Health status
190 | Beaudry, M.,Dufour, R.,Marcoux, S. Reaction between infant feeding and infections during the first six months of life. Journal of Pediatrics. 1995;126(2):191-197. | Study design
191 | Beaudry, M.,Dufour, R.,Marcoux, S. Relation between infant feeding and infections during the first six months of life. J Pediatr. 1995;126(2):191-7. | Study design
192 | Beaver, K. M.,Vaughn, M. G.,DeLisi, M.,Higgins, G. E. The biosocial correlates of neuropsychological deficits: results from the national longitudinal study of adolescent health. Int J Offender Ther Comp Criminol. 2010;54(6):878-94. | Included for systematic reviews not completed
193 | Becher, J. C.,Bhushan, S. S.,Lyon, A. J. Unexpected collapse in apparently healthy newborns--a prospective national study of a missing cohort of neonatal deaths and near-death events. Arch Dis Child Fetal Neonatal Ed. 2012;97(1):F30-4. | Study design
194 | Beebe, D. W.,Rausch, J.,Byars, K. C.,Lanphear, B.,Yolton, K. Persistent snoring in preschool children: predictors and behavioral and developmental correlates. Pediatrics. 2012;130(3):382-9. | Independent variable, Dependent variable
195 | Beentjes VE,Weerheijm KL,Groen HJ. Factors involved in the aetiology of molar-incisor hypomineralisation (MIH). Eur J Paediatr Dent. 2002;3:9-13. | Study design
196 | Beilin, L.,Huang, R. C. Childhood obesity, hypertension, the metabolic syndrome and adult cardiovascular disease. Clin Exp Pharmacol Physiol. 2008;35(4):409-11. | Study design
197 | Belfort, M. B.,Rifas-Shiman, S. L.,Kleinman, K. P.,Guthrie, L. B.,Bellinger, D. C.,Taveras, E. M.,Gillman, M. W.,Oken, E. Infant feeding and childhood cognition at ages 3 and 7 years: Effects of breastfeeding duration and exclusivity. JAMA Pediatr. 2013;167(9):836-44. | Included for systematic reviews not completed
198 | Belfort, M. B.,Rifas-Shiman, S. L.,Rich-Edwards, J. W.,Kleinman, K. P.,Oken, E.,Gillman, M. W. Infant growth and child cognition at 3 years of age. Pediatrics. 2008;122(3):e689-95. | Independent variable
199 | Ben, X. M.,Zhou, X. Y.,Zhao, W. H.,Yu, W. L.,Pan, W.,Zhang, W. L.,Wu, S. M.,Van Beusekom, C. M.,Schaafsma, A. Growth and development of term infants fed with milk with long-chain polyunsaturated fatty acid supplementation. Chinese Medical Journal. 2004;117(8):1268-1270. | Independent variable
200 | Bener, A.,Alsaied, A.,Al-Ali, M.,Al-Kubaisi, A.,Basha, B.,Abraham, A.,Guiter, G.,Mian, M. High prevalence of vitamin D deficiency in type 1 diabetes mellitus and healthy children. Acta Diabetol. 2009;46(3):183-9. | Study design
201 | Bener, A.,Denic, S.,Galadari, S. Longer breast-feeding and protection against childhood leukaemia and lymphomas. Eur J Cancer. 2001;37(2):234-8. | Independent variable
202 | Benn, C. S.,Wohlfahrt, J.,Aaby, P.,Westergaard, T.,Benfeldt, E.,Michaelsen, K. F.,Bjorksten, B.,Melbye, M. Breastfeeding and risk of atopic dermatitis, by parental history of allergy, during the first 18 months of life. Am J Epidemiol. 2004;160(3):217-23. | Independent variable
203 | Bennett, K. E.,Haggard, M. P. Accumulation of factors influencing children’s middle ear disease: risk factor modelling on a large population cohort. J Epidemiol Community Health. 1998;52(12):786-93. | Study design, Dependent variable
204 | Berger, R.,Hadziselimovic, F.,Just, M.,Reigel, P. Effect of feeding human milk on nosocomial rotavirus infections in an infants ward. Dev Biol Stand. 1983;53:219-28. | Study design, Health status
205 | Bergmann, K. E.,Bergmann, R. L.,Von Kries, R.,Bohm, O.,Richter, R.,Dudenhausen, J. W.,Wahn, U. Early determinants of childhood overweight and adiposity in a birth cohort study: role of breast-feeding. Int J Obes Relat Metab Disord. 2003;27(2):162-72. | Independent variable
206 | Bergmann, R. L.,Bergler, H.,Moshoudis, E.,Bergmann, K. E.,Lachmann, E. Prevention of iron deficiency of breast-fed babies by using suitable additional food, a prospective, controlled study. Monatsschrift fur Kinderheilkunde. 1988;136:491. | Language, Study design
207 | Bergmann, R. L.,Bergmann, K. E.,Lau-Schadensdorf, S.,Luck, W.,Dannemann, A.,Bauer, C. P.,Dorsch, W.,Forster, J.,Schmidt, E.,Schulz, J.,et al.,. Atopic diseases in infancy. The German multicenter atopy study (MAS-90). Pediatr Allergy Immunol. 1994;5(6 Suppl):19-25. | Independent variable
208 | Bergstrom, A.,Skov, T. H.,Bahl, M. I.,Roager, H. M.,Christensen, L. B.,Ejlerskov, K. T.,Molgaard, C.,Michaelsen, K. F.,Licht, T. R. Establishment of intestinal microbiota during early life: a longitudinal, explorative study of a large cohort of Danish infants. Appl Environ Microbiol. 2014;80(9):2889-900. | Dependent variable
209 | Bergstrom, E.,Hernell, O.,Persson, L. A.,Vessby, B. Serum lipid values in adolescents are related to family history, infant feeding, and physical growth. Atherosclerosis. 1995;117(1):1-13. | Independent variable
210 | Beristain-Manterola, R.,Pasquetti-Ceccatelli, A.,Meléndez-Mier, G.,Sánchez-Escobar, O. A.,Cuevas-Covarrubias, S. A. Evaluation of iron status in healthy six-month-old infants in Mexican population: Evidence of a high prevalence of iron deficiency. e-SPEN. 2010;5(1):e37-e39. | Study design
211 | Berkowitz, C. D.,Uchiyama, N.,Tully, S. B.,Marble, R. D.,Spencer, M.,Stein, M. T.,Orr, D. P. Fever in infants less than two months of age: spectrum of disease and predictors of outcome. Pediatr Emerg Care. 1985;1(3):128-35. | Study design, Health status
212 | Berkowitz, R. J. Streptococcus mutans and dental caries in infants. Compend Contin Educ Dent. 1985;6(6):463-6. | Study design
213 | Bernard, A.,Nickmilder, M. Association of breastfeeding with higher serum inhibin B level at adolescence. JAMA Pediatr. 2013;167(9):869-70. | Study design, Dependent variable
214 | Bernard, J. Y.,Armand, M.,Garcia, C.,Forhan, A.,De Agostini, M.,Charles, M. A.,Heude, B. The association between linoleic acid levels in colostrum and child cognition at 2 and 3 y in the EDEN cohort. Pediatr Res. 2015;77(6):829-35. | Included for systematic reviews not completed
215 | Bernard, J. Y.,De Agostini, M.,Forhan, A.,Alfaiate, T.,Bonet, M.,Champion, V.,Kaminski, M.,de Lauzon-Guillain, B.,Charles, M. A.,Heude, B. Breastfeeding duration and cognitive development at 2 and 3 years of age in the EDEN mother-child cohort. J Pediatr. 2013;163(1):36-42 e1. | Included for systematic reviews not completed
216 | Bernard, J. Y.,De Agostini, M.,Forhan, A.,de Lauzon-Guillain, B.,Charles, M. A.,Heude, B. The dietary n6:n3 fatty acid ratio during pregnancy is inversely associated with child neurodevelopment in the EDEN mother-child cohort. J Nutr. 2013;143(9):1481-8. | Included for systematic reviews not completed
217 | Bernardi, J. R.,Gama, C. M.,Vitolo, M. R. An infant feeding update program at healthcare centers and its impact on breastfeeding and morbidity. Cadernos de Saude Publica. 2011;27(6):1213-1222. | Language
218 | Berseth, C. L.,Mitmesser, S. H.,Birch, E.,Khoury, J.,Bean, J.,Harris, C.,Scalabrin, D. Intake of DHA/ARA via breast milk or formula supplementation during infancy can affect the incidence and recurrence of allergic manifestations in young children. Journal of Pediatric Gastroenterology and Nutrition. Conference: European Society for Paediatric Gastroenterology, Hepatology, and Nutrition Annual Meeting 2011 Sorrento Italy. Conference Start: 20110525 Conference End: 20110528. Conference Publication: (var.pagings). 2011;52(Suppl 2):E61. | Peer review
219 | Betoko, A.,Charles, M. A.,Hankard, R.,Forhan, A.,Bonet, M.,Regnault, N.,Botton, J.,Saurel-Cubizolles, M. J.,de Lauzon-Guillain, B. Determinants of infant formula use and relation with growth in the first 4 months. Matern Child Nutr. 2014;10(2):267-79. | Included for systematic reviews not completed
220 | Betran, A. P.,de Onis, M.,Lauer, J. A.,Villar, J. Ecological study of effect of breast feeding on infant mortality in Latin America. Bmj. 2001;323(7308):303-6. | Study design
221 | Beyerlein, A.,Fahrmeir, L.,Mansmann, U.,Toschke, A. M. Alternative regression models to assess increase in childhood BMI. BMC Med Res Methodol. 2008;8:59. | Study design
222 | Bhan, M. K.,Arora, N. K.,Singh, K. D. Management of persistent diarrhea during infancy in clinical practice. Indian J Pediatr. 1991;58(6):769-74. | Study design, Country
223 | Bhatia, B. D.,Banerjee, D.,Agarwal, D. K.,Agarwal, K. N. Exterogestate growth: relationship with maternal body size and dietary intakes. Indian J Pediatr. 1983;50(404):241-6. | Study design, Country
224 | Bianchi, C.,Brambilla, P.,Cella, D.,Ragogna, F.,Tettamanti, C.,Del Puppo, M.,Kienle, M. G.,Chiumello, G.,Ruotolo, G. Influence of breast- and formula-feeding on plasma cholesterol precursor sterols throughout the first year of life. J Pediatr. 1997;131(6):928-31. | Group size
225 | Biering-Sorensen F,Hilden J,Biering-Sorensen K. Breast-feeding and infant health in Copenhagen 1941-1972. Dan Med Bull. 1983;30:36-41. | Study design, Dependent variable
226 | Biesbroek, G.,Bosch, A. A.,Wang, X.,Keijser, B. J.,Veenhoven, R. H.,Sanders, E. A.,Bogaert, D. The impact of breastfeeding on nasopharyngeal microbial communities in infants. Am J Respir Crit Care Med. 2014;190(3):298-308. | Dependent variable
227 | Biesbroek, G.,Tsivtsivadze, E.,Sanders, E. A.,Montijn, R.,Veenhoven, R. H.,Keijser, B. J.,Bogaert, D. Early respiratory microbiota composition determines bacterial succession patterns and respiratory health in children. Am J Respir Crit Care Med. 2014;190(11):1283-92. | Study design, Dependent variable
228 | Bilenko, N.,Fraser, D.,Naggan, L. Maternal knowledge and environmental factors associated with risk of diarrhea in Israeli Bedouin children. Eur J Epidemiol. 1999;15(10):907-12. | Independent variable
229 | Bindon, J. R. The influence of infant feeding patterns on growth of children in American Samoa. Med Anthropol. 1985;9(2):183-95. | Independent variable
230 | Binns C,James J,Lee MK. Trends in asthma, allergy and breastfeeding in Australia. Breastfeed Rev. 2013;21:7-8. | Study design
231 | Bioavailability of milk zinc in infants. Nutr Rev. 1984;42:220-2. | Study design
232 | Birch, E. E.,Garfield, S.,Castaneda, Y.,Hughbanks-Wheaton, D.,Uauy, R.,Hoffman, D. Visual acuity and cognitive outcomes at 4 years of age in a double-blind, randomized trial of long-chain polyunsaturated fatty acid-supplemented infant formula. Early Hum Dev. 2007;83(5):279-84. | Included for systematic reviews not completed
233 | Birch, E. E.,Hoffman, D. R.,Uauy, R.,Birch, D. G.,Prestidge, C. Visual acuity and the essentiality of docosahexaenoic acid and arachidonic acid in the diet of term infants. Pediatr Res. 1998;44(2):201-9. | Group size
234 | Birkbeck, J. A.,Buckfield, P. M.,Silva, P. A. Lack of long-term effect of the method of infant feeding on growth. Hum Nutr Clin Nutr. 1985;39(1):39-44. | Independent variable
235 | Birkett, D. On bottle versus breast. Health Serv J. 2005;115(5957):19. | Study design
236 | Bisgaard, H.,Halkjær, L. B.,Hinge, R.,Giwercman, C.,Palmer, C.,Silveira, L.,Strand, M. Risk analysis of early childhood eczema. Journal of Allergy and Clinical Immunology. 2009;123(6):1355-1360.e5. | Independent variable
237 | Bishara, S. E.,Nowak, A. J.,Kohout, F. J.,Heckert, D. A.,Hogan, M. M. Influence of feeding and non-nutritive sucking methods on the development of the dental arches: longitudinal study of the first 18 months of life. Pediatr Dent. 1987;9(1):13-21. | Independent variable
238 | Bishara, S. E.,Warren, J. J.,Broffitt, B.,Levy, S. M. Changes in the prevalence of nonnutritive sucking patterns in the first 8 years of life. Am J Orthod Dentofacial Orthop. 2006;130(1):31-6. | Independent variable
239 | Bishop, W. S. Weaning the breast-fed toddler or preschooler. Pediatr Nurs. 1985;11(3):211-4. | Study design
240 | Bjorke-Monsen, A. L. Is exclusive breastfeeding ensuring an optimal micronutrient status and psychomotor development in infants?. Clin Biochem. 2014;47(9):714. | Study design
241 | Bjorksten, B.,Ait-Khaled, N.,Innes Asher, M.,Clayton, T. O.,Robertson, C. Global analysis of breast feeding and risk of symptoms of asthma, rhinoconjunctivitis and eczema in 6-7 year old children: ISAAC Phase Three. Allergol Immunopathol (Madr). 2011;39(6):318-25. | Study design
242 | Blake, P. A.,Ramos, S.,MacDonald, K. L.,Rassi, V.,Gomes, T. A.,Ivey, C.,Bean, N. H.,Trabulsi, L. R. Pathogen-specific risk factors and protective factors for acute diarrheal disease in urban Brazilian infants. J Infect Dis. 1993;167(3):627-32. | Independent variable, Health status
243 | Blattner, C. M.,Murase, J. E. A practice gap in pediatric dermatology: does breast-feeding prevent the development of infantile atopic dermatitis?. J Am Acad Dermatol. 2014;71(2):405-6. | Study design
244 | Bloom, K.,Goldbloom, R. B.,Robinson, S. C.,Stevens, F. E. Breast versus formula feeding. Acta Paediatr Scand Suppl. 1982;300:1-26. | Study design, Dependent variable
245 | Bocca, B.,Alimonti, A.,Giglio, L.,Di Pasquale, M.,Caroli, S.,Ambruzzi, M. A.,Bocca, A. P.,Coni, E. Nutritive significance of element speciation in breast milk. The case of calcium, copper, iron, magnesium, manganese, and zinc. Adv Exp Med Biol. 2000;478:385-6. | Study design, Dependent variable
246 | Boccolini, C. S.,Carvalho, M. L.,Oliveira, M. I.,Boccolini Pde, M. Breastfeeding can prevent hospitalization for pneumonia among children under 1 year old. J Pediatr (Rio J). 2011;87(5):399-404. | Study design, Independent variable
247 | Boccolini, C. S.,Carvalho, M. L.,Oliveira, M. I.,Perez-Escamilla, R. Breastfeeding during the first hour of life and neonatal mortality. J Pediatr (Rio J). 2013;89(2):131-6. | Study design
248 | Bodington, M. J.,McNally, P. G.,Burden, A. C. Cow’s milk and type 1 childhood diabetes: no increase in risk. Diabet Med. 1994;11(7):663-5. | Independent variable
249 | Boediman, D.,Murakami, R.,Nakamura, H.,Matsuo, T. Plasma apolipoprotein and lipid profiles in infants in the first year of life. Kobe J Med Sci. 1989;35(3):165-76. | Group size
250 | Boerma, J. T.,Bicego, G. T. Preceding birth intervals and child survival: searching for pathways of influence. Stud Fam Plann. 1992;23(4):243-56. | Study design, Independent variable
251 | Bogen, D. L.,Hanusa, B. H.,Whitaker, R. C. The effect of breast-feeding with and without formula use on the risk of obesity at 4 years of age. Obes Res. 2004;12(9):1527-35. | Included for systematic reviews not completed
252 | Bognetti, E.,Meschi, F.,Malavasi, C.,Pastore, M. R.,Sergi, A.,Illeni, M. T.,Maffeis, C.,Pinelli, L.,Chiumello, G. HLA-antigens in Italian type 1 diabetic patients: role of DR3/DR4 antigens and breast feeding in the onset of the disease. Acta Diabetol. 1992;28(3-4):229-32. | Dependent variable
253 | Bolanos, A. V.,Caire, G.,Valencia, M. E.,Casanueva, E.,Roman Perez, R.,Calderon de la Barca, A. M. Energy intake and growth of breast-fed infants in two regions of Mexico. Adv Exp Med Biol. 2000;478:371-2. | Study design
254 | Bond, S. Randomized trial provides strong evidence that prolonged, exclusive breastfeeding enhances cognitive development in children. Journal of Midwifery & Women’s Health. 2008;53(5):472-473 2p. | Study design
255 | Bonuck, K. A.,Freeman, K.,Trombley, M. Randomized controlled trial of a prenatal and postnatal lactation consultant intervention on infant health care use. Arch Pediatr Adolesc Med. 2006;160(9):953-60. | Included for systematic reviews not completed
256 | Bonuck, K.,Avraham, S. B.,Lo, Y.,Kahn, R.,Hyden, C. Bottle-weaning intervention and toddler overweight. J Pediatr. 2014;164(2):306-12 e1-2. | Independent variable, Dependent variable
257 | Boonyaratavej, N.,Suriyawongpaisal, P.,Takkinsatien, A.,Wanvarie, S.,Rajatanavin, R.,Apiyasawat, P. Physical activity and risk factors for hip fractures in Thai women. Osteoporos Int. 2001;12(3):244-8. | Independent variable, Age
258 | Bordeaux, D. R.,Heidenreich, J. G.,Schlagheck, D. J.,Crabtree, J. T.,Trachtenbarg, D. E. Infant nutrition. J Fam Pract. 1982;14(1):145-50. | Study design
259 | Borgnolo, G.,Barbone, F.,Scornavacca, G.,Franco, D.,Vinci, A.,Iuculano, F. A case-control study of Salmonella gastrointestinal infection in Italian children. Acta Paediatr. 1996;85(7):804-8. | Health status
260 | Bornhorst, C.,Siani, A.,Russo, P.,Kourides, Y.,Sion, I.,Molnar, D.,Moreno, L. A.,Rodriguez, G.,Ben-Shlomo, Y.,Howe, L.,Lissner, L.,Mehlig, K.,Regber, S.,Bammann, K.,Foraita, R.,Ahrens, W.,Tilling, K. Early Life Factors and Inter-Country Heterogeneity in BMI Growth Trajectories of European Children: The IDEFICS Study. PLoS One. 2016;11(2):e0149268. | Included for systematic reviews not completed
261 | Bortolini, G. A.,Vitolo, M. R. The impact of systematic dietary counseling during the first year of life on prevalence rates of anemia and iron deficiency at 12-16 months. J Pediatr (Rio J). 2012;88(1):33-9. | Included for systematic reviews not completed
262 | Boshuizen, H. C.,Verkerk, P. H.,Reerink, J. D.,Herngreen, W. P.,Zaadstra, B. M.,Verloove-Vanhorick, S. P. Maternal smoking during lactation: relation to growth during the first year of life in a Dutch birth cohort. Am J Epidemiol. 1998;147(2):117-26. | Independent variable
263 | Boskabadi, H.,Ramazanzadeh, M.,Zakerihamidi, M.,Omran, F. R. Risk factors of breast problems in mothers and its effects on newborns. Iranian Red Crescent Medical Journal. 2014;16(6). | Independent variable, Dependent variable
264 | Boulton, J. Nutrition in childhood and its relationships to early somatic growth, body fat, blood pressure, and physical fitness. Acta Paediatr Scand Suppl. 1981;284:1-85. | Study design
265 | Boutwell, B. B.,Beaver, K. M.,Barnes, J. C. Role of breastfeeding in childhood cognitive development: a propensity score matching analysis. J Paediatr Child Health. 2012;48(9):840-5. | Included for systematic reviews not completed
266 | Bouwstra, H.,Boersma, E. R.,Boehm, G.,Dijck-Brouwer, D. A.,Muskiet, F. A.,Hadders-Algra, M. Exclusive breastfeeding of healthy term infants for at least 6 weeks improves neurological condition. J Nutr. 2003;133(12):4243-5. | Included for systematic reviews not completed
267 | Bouwstra, H.,Dijck-Brouwer, D. A.,Boehm, G.,Boersma, E. R.,Muskiet, F. A.,Hadders-Algra, M. Long-chain polyunsaturated fatty acids and neurological developmental outcome at 18 months in healthy term infants. Acta Paediatr. 2005;94(1):26-32. | Included for systematic reviews not completed
268 | Bouwstra, H.,Dijck-Brouwer, D. A.,Wildeman, J. A.,Tjoonk, H. M.,van der Heide, J. C.,Boersma, E. R.,Muskiet, F. A.,Hadders-Algra, M. Long-chain polyunsaturated fatty acids have a positive effect on the quality of general movements of healthy term infants. Am J Clin Nutr. 2003;78(2):313-8. | Independent variable
269 | Bouwstra, H.,Dijck-Brouwer, J.,Decsi, T.,Boehm, G.,Boersma, E. R.,Muskiet, F. A.,Hadders-Algra, M. Neurologic condition of healthy term infants at 18 months: positive association with venous umbilical DHA status and negative association with umbilical trans-fatty acids. Pediatr Res. 2006;60(3):334-9. | Independent variable
270 | Bove, I.,Campoy, C.,Uauy, R.,Miranda, T.,Cerruti, F. Trends in early growth indices in the first 24 months of life in Uruguay over the past decade. J Health Popul Nutr. 2014;32(4):600-7. | Study design
271 | Bradley, C. K.,Hillman, L.,Sherman, A. R.,Leedy, D.,Cordano, A. Evaluation of two iron-fortified, milk-based formulas during infancy. Pediatrics. 1993;91(5):908-14. | Included for systematic reviews not completed
272 | Braga GC, Ferriolli E, Quintana SM, Ferriani RA, Pfrimer K, Vieira CS. Immediate Post-Partum Initiation of Etonogestrel-Releasing Implant: A Randomized Controlled Trial on Breastfeeding Impact. Obstet Gynecol Survey. 2015;70:702-4. | Study design
273 | Bramhagen, A. C.,Svahn, J.,Hallstrom, I.,Axelsson, I. Factors influencing iron nutrition among one-year-old healthy children in Sweden. J Clin Nurs. 2011;20(13-14):1887-94. | Study design
274 | Brams, M.,Maloney, J. “Nursing bottle caries” in breast-fed children. J Pediatr. 1983;103(3):415-6. | Study design
275 | Brandenburg, A. H.,Jeannet, P. Y.,Steensel-Moll, H. A.,Ott, A.,Rothbarth, P. H.,Wunderli, W.,Suter, S.,Neijens, H. J.,Osterhaus, A. D.,Siegrist, C. A. Local variability in respiratory syncytial virus disease severity. Arch Dis Child. 1997;77(5):410-4. | Study design, Health status
276 | Brandstrom, A.,Brostrom, G.,Persson, L. A. The impact of feeding patterns on infant mortality in a nineteenth century Swedish parish. J Trop Pediatr. 1984;30(3):154-9. | Study design, Independent variable
277 | Bray, K. K.,Branson, B. G.,Williams, K. Early childhood caries in an urban health department: an exploratory study. J Dent Hyg. 2003;77(4):225-32. | Study design
278 | Breast feeding and child development at five years. Nutr Rev. 1985;43:173-4. | Study design
279 | Breast feeding seems to reduce the risk of obesity in children. Bmj. 1999;319(7203):B. | Study design
280 | Breast feeding: benefits and hazards. Early Hum Dev. 1997;49 Suppl:S1-203. | Study design
281 | Breast versus bottle: an in-house debate. Midwife Health Visit Community Nurse. 1988;24(7):254-5. | Study design
282 | Breast-feeding and human milk. Eur J Obstet Gynecol Reprod Biol. 1983;15(4-6):385-94. | Study design
283 | Breastfeeding could be linked to higher IQ. Perspect Public Health. 2015;135(3):114. | Study design
284 | Breastfeeding for the health of baby and mother. Nurs J India. 2011;102(8):179. | Study design
285 | Breastfeeding study looks at behaviour. Midwives. 2012;15(1):9-9 1p. | Study design
286 | Breastfeeding. Nurs Womens Health. 2015;19(1):83-8. | Study design
287 | Breastfeeding: sensitive mothers and intelligent offspring. Arch Dis Child. 2015;100(6):601. | Study design
288 | Brew, B. K.,Kull, I.,Garden, F.,Almqvist, C.,Bergstrom, A.,Lind, T.,Webb, K.,Wickman, M.,Marks, G. B. Breastfeeding, asthma, and allergy: a tale of two cities. Pediatr Allergy Immunol. 2012;23(1):75-82. | Study design
289 | Brew, B. K.,Marks, G. B.,Almqvist, C.,Cistulli, P. A.,Webb, K.,Marshall, N. S. Breastfeeding and snoring: a birth cohort study. PLoS One. 2014;9(1):e84956. | Dependent variable
290 | Briggs, D. Baby milks and the EC. Infant nutrition. Nurs Times. 1992;88(32):24-6. | Study design
291 | Brion, M. J. A.,Lawlor, D. A.,Matijasevich, A.,Horta, B.,Anselmi, L.,Araújo, C. L.,Menezes, A. M. B.,Victora, C. G.,Smith, G. D. What are the causal effects of breastfeeding on IQ, obesity and blood pressure? Evidence from comparing high-income with middle-income cohorts. International Journal of Epidemiology. 2011;40(3):670-680. | Independent variable
292 | Broad, F. E.,Duganzich, D. M. The effects of infant feeding, birth order, occupation and socio-economic status on speech in six-year-old children. N Z Med J. 1983;96(734):483-6. | Independent variable
293 | Brodish, M. S. Relationship of early bonding to initial infant feeding patterns in bottle-fed newborns. JOGN Nurs. 1982;11(4):248-52. | Independent variable
294 | Brooks, J. G.,Gilbert, R. E.,Flemming, P. J.,Berry, P. J.,Golding, J. Postnatal growth preceding sudden infant death syndrome. Pediatrics. 1994;94(4 Pt 1):456-61. | Included for systematic reviews not completed
295 | Broor, S.,Pandey, R. M.,Ghosh, M.,Maitreyi, R. S.,Lodha, R.,Singhal, T.,Kabra, S. K. Risk factors for severe acute lower respiratory tract infection in under-five children. Indian Pediatr. 2001;38(12):1361-9. | Country
296 | Brown, A.,Lee, M. Breastfeeding during the first year promotes satiety responsiveness in children aged 18-24 months. Pediatr Obes. 2012;7(5):382-90. | Included for systematic reviews not completed
297 | Brown, J. P.,Junner, C.,Liew, V. A study of Streptococcus mutans levels in both infants with bottle caries and their mothers. Aust Dent J. 1985;30(2):96-8. | Independent variable
298 | Brown, K. H.,Black, R. E.,Lopez de Romana, G.,Creed de Kanashiro, H. Infant-feeding practices and their relationship with diarrheal and other diseases in Huascar (Lima), Peru. Pediatrics. 1989;83(1):31-40. | Independent variable
299 | Brown, K. H.,Stallings, R. Y.,de Kanashiro, H. C.,Lopez de Romana, G.,Black, R. E. Effects of common illnesses on infants’ energy intakes from breast milk and other foods during longitudinal community-based studies in Huascar (Lima), Peru. Am J Clin Nutr. 1990;52(6):1005-13. | Dependent variable
300 | Broxton, D. Infant feeding research summaries. International Journal of Childbirth Education. 2008;23(2):28-31 4p. | Country
301 | Bruce, L.,Lieberman, L. S. Nutritional anthropometry and dietary intake of children from the Las Cuevas region of the Dominican Republic. Arch Latinoam Nutr. 1987;37(2):250-8. | Study design
302 | Bruerd, B.,Kinney, M. B.,Bothwell, E. Preventing baby bottle tooth decay in American Indian and Alaska native communities: a model for planning. Public Health Rep. 1989;104(6):631-40. | Independent variable
303 | Bruno, G.,Milita, O.,Ferrara, M.,Nisini, R.,Cantani, A.,Businco, L. Prevention of atopic diseases in high risk babies (long-term follow-up). Allergy Proc. 1993;14(3):181-6; discussion 186-7. | Independent variable
304 | Brunser, O.,Espinoza, J.,Figueroa, G.,Araya, M.,Spencer, E.,Hilpert, H.,Link-Amster, H.,Brussow, H. Field trial of an infant formula containing anti-rotavirus and anti-Escherichia coli milk antibodies from hyperimmunized cows. J Pediatr Gastroenterol Nutr. 1992;15(1):63-72. | Independent variable
305 | Buckley, K. M. Long-term breastfeeding: nourishment or nurturance?. J Hum Lact. 2001;17(4):304-12. | Study design, Independent variable
306 | Buinauskiene, J.,Baliutaviciene, D.,Zalinkevicius, R. Glucose tolerance of 2- to 5-yr-old offspring of diabetic mothers. Pediatric Diabetes. 2004;5(3):143-146. | Independent variable
307 | Bulk-Bunschoten, A. M.,Pasker-de Jong, P. C.,van Wouwe, J. P.,de Groot, C. J. Ethnic variation in infant-feeding practices in the Netherlands and weight gain at 4 months. J Hum Lact. 2008;24(1):42-9. | Independent variable, Dependent variable
308 | Bulk-Bunschoten, A. M.,van Bodegom, S.,Reerink, J. D.,de Jong, P. C.,de Groot, C. J. Weight and weight gain at 4 months (The Netherlands 1998): influences of nutritional practices, socio-economic and ethnic factors. Paediatr Perinat Epidemiol. 2002;16(4):361-9. | Independent variable
309 | Bulkow, L. R.,Singleton, R. J.,DeByle, C.,Miernyk, K.,Redding, G.,Hummel, K. B.,Chikoyak, L.,Hennessy, T. W. Risk factors for hospitalization with lower respiratory tract infections in children in rural Alaska. Pediatrics. 2012;129(5):e1220-7. | Included for systematic reviews not completed
310 | Bulkow, L. R.,Singleton, R. J.,Karron, R. A.,Harrison, L. H. Risk factors for severe respiratory syncytial virus infection among Alaska native children. Pediatrics. 2002;109(2):210-6. | Included for systematic reviews not completed
311 | Bunik, M.,Shobe, P.,O’Connor, M. E.,Beaty, B.,Langendoerfer, S.,Crane, L. Randomized controlled trial to evaluate a telephone support intervention for breastfeeding in low-income Latina mothers. Breastfeeding medicine. 2007;2(3):183. | Study design
312 | Burdette, H. L.,Whitaker, R. C. Differences by race and ethnicity in the relationship between breastfeeding and obesity in preschool children. Ethn Dis. 2007;17(3):467-70. | Included for systematic reviews not completed
313 | Burdette, H. L.,Whitaker, R. C.,Hall, W. C.,Daniels, S. R. Breastfeeding, introduction of complementary foods, and adiposity at 5 y of age. Am J Clin Nutr. 2006;83(3):550-8. | Included for systematic reviews not completed
314 | Burke, V.,Beilin, L. J.,Simmer, K.,Oddy, W. H.,Blake, K. V.,Doherty, D.,Kendall, G. E.,Newnham, J. P.,Landau, L. I.,Stanley, F. J. Breastfeeding and overweight: longitudinal analysis in an Australian birth cohort. J Pediatr. 2005;147(1):56-61. | Included for systematic reviews not completed
315 | Burns, E.,Schmied, V.,Sheehan, A.,Fenwick, J. Let women express themselves - breastfeeding study. Australian Nursing Journal. 2009;17(2):44-45 2p. | Study design
316 | Businco, L.,Marchetti, F.,Pellegrini, G.,Cantani, A.,Perlini, R. Prevention of atopic disease in “at-risk newborns” by prolonged breast-feeding. Ann Allergy. 1983;51(2 Pt 2):296-9. | Independent variable
317 | Butland, B. K.,Strachan, D. P.,Lewis, S.,Bynner, J.,Butler, N.,Britton, J. Investigation into the increase in hay fever and eczema at age 16 observed between the 1958 and 1970 British birth cohorts. BMJ. 1997;315(7110):717-21. | Independent variable
318 | Butte, N. F. Impact of infant feeding practices on childhood obesity. Journal of Nutrition. 2009;139(2):412S-416S. | Study design
319 | Butte, N. F.,Smith, E. O.,Garza, C. Energy utilization of breast-fed and formula-fed infants. Am J Clin Nutr. 1990;51(3):350-8. | Independent variable
320 | Butte, N. F.,Wong, W. W.,Ferlic, L.,Smith, E. O.,Klein, P. D.,Garza, C. Energy expenditure and deposition of breast-fed and formula-fed infants during early infancy. Pediatr Res. 1990;28(6):631-40. | Study design
321 | Butte, N. F.,Wong, W. W.,Hopkinson, J. M.,Smith, E. O.,Ellis, K. J. Infant feeding mode affects early growth and body composition. Pediatrics. 2000;106(6):1355-66. | Included for systematic reviews not completed
322 | Butters, L.,McCabe, R. The influence of breast and bottle feeding on blood pressure. Midwifery. 1988;4(3):130-2. | Study design, Dependent variable
323 | Buyken, A. E.,Karaolis-Danckert, N.,Remer, T.,Bolzenius, K.,Landsberg, B.,Kroke, A. Effects of breastfeeding on trajectories of body fat and BMI throughout childhood. Obesity (Silver Spring). 2008;16(2):389-95. | Included for systematic reviews not completed
324 | Bystrova, K.,Matthiesen, A. S.,Widstrom, A. M.,Ransjo-Arvidson, A. B.,Welles-Nystrom, B.,Vorontsov, I.,Uvnas-Moberg, K. The effect of Russian Maternity Home routines on breastfeeding and neonatal weight loss with special reference to swaddling. Early Hum Dev. 2007;83(1):29-39. | Study design, Independent variable
325 | Cable, N.,Bartley, M.,McMunn, A.,Kelly, Y. 011 Gender differences in the effect of breast feeding on adult psychological well-being. Journal of Epidemiology & Community Health. 2010;64:A4-5 1p. | No full text
326 | Cable, N.,Bartley, M.,McMunn, A.,Kelly, Y. Gender differences in the effect of breastfeeding on adult psychological well-being. Eur J Public Health. 2012;22(5):653-8. | Included for systematic reviews not completed
327 | Cai, S.,Pang, W. W.,Low, Y. L.,Sim, L. W.,Sam, S. C.,Bruntraeger, M. B.,Wong, E. Q.,Fok, D.,Broekman, B. F.,Singh, L.,Richmond, J.,Agarwal, P.,Qiu, A.,Saw, S. M.,Yap, F.,Godfrey, K. M.,Gluckman, P. D.,Chong, Y. S.,Meaney, M. J.,Kramer, M. S.,Rifkin-Graboi, A. Infant feeding effects on early neurocognitive development in Asian children. Am J Clin Nutr. 2015;101(2):326-36. | Included for systematic reviews not completed
328 | Calamaro, C. J. Infant nutrition in the first year of life: tradition or science?. Pediatr Nurs. 2000;26(2):211-5. | Study design
329 | Calvo, E. B.,Galindo, A. C.,Aspres, N. B. Iron status in exclusively breast-fed infants. Pediatrics. 1992;90(3 I):375-379. | Group size
330 | Cama, R. I.,Parashar, U. D.,Taylor, D. N.,Hickey, T.,Figueroa, D.,Ortega, Y. R.,Romero, S.,Perez, J.,Sterling, C. R.,Gentsch, J. R.,Gilman, R. H.,Glass, R. I. Enteropathogens and other factors associated with severe disease in children with acute watery diarrhea in Lima, Peru. Journal of Infectious Diseases. 1999;179(5):1139-1144. | Health status
331 | Camara, A. A.,Silva, J. M.,Ferriani, V. P.,Tobias, K. R.,Macedo, I. S.,Padovani, M. A.,Harsi, C. M.,Cardoso, M. R.,Chapman, M. D.,Arruda, E.,Platts-Mills, T. A.,Arruda, L. K. Risk factors for wheezing in a subtropical environment: role of respiratory viruses and allergen sensitization. J Allergy Clin Immunol. 2004;113(3):551-7. | Dependent variable
332 | Camargo-Figuera, F. A.,Barros, A. J.,Santos, I. S.,Matijasevich, A.,Barros, F. C. Early life determinants of low IQ at age 6 in children from the 2004 Pelotas Birth Cohort: a predictive approach. BMC Pediatr. 2014;14:308. | Included for systematic reviews not completed
333 | Cameron M,Hofvander Y. Problems associated with breast-milk substitutes. Nurs J India. 1984;75:245-6, 247, 249-50. | Study design
334 | Cameron, S. L.,Gray, A. R.,Taylor, R. W.,Lawrence, J. A.,Galland, B. C.,Hanna, M. B.,Heath, A. L. M.,Sayers, R. M.,Taylor, B. J. Excessive growth from 6 to 24 months of age: Results from the prevention of overweight in infancy (POI) randomised controlled trial. Archives of disease in childhood. 2014;99:A109. | No full text
335 | Campbell N. The nutritional and immunological benefits of breast milk. Aust Nurses J. 1981;10:40-3, 47. | Study design
336 | Campus, G.,Solinas, G.,Sanna, A.,Maida, C.,Castiglia, P. Determinants of ECC in Sardinian preschool children. Community Dent Health. 2007;24(4):253-6. | Independent variable
337 | Camurdan, M. O.,Camurdan, A. D.,Polat, S.,Beyazova, U. Growth patterns of large, small, and appropriate for gestational age infants: impacts of long-term breastfeeding: a retrospective cohort study. J Pediatr Endocrinol Metab. 2011;24(7-8):463-8. | Independent variable
338 | Cant, A. J.,Bailes, J. A. How should we feed the potentially allergic infant?. Hum Nutr Appl Nutr. 1984;38(6):474-6. | Study design
339 | Cantani, A.,Micera, M. Neonatal cow milk sensitization in 143 case-reports: role of early exposure to cow’s milk formula. Eur Rev Med Pharmacol Sci. 2005;9(4):227-30. | Study design, Health status
340 | Cantey, J. B.,Bascik, S. L.,Heyne, N. G.,Gonzalez, J. R.,Jackson, G. L.,Rogers, V. L.,Sheffield, J. S.,Trevino, S.,Sendelbach, D.,Wendel, G. D.,Sanchez, P. J. Prevention of mother-to-infant transmission of influenza during the postpartum period. Am J Perinatol. 2013;30(3):233-40. | Study design, Independent variable
341 | Capeding, R.,Gepanayao, C. P.,Calimon, N.,Lebumfacil, J.,Davis, A. M.,Stouffer, N.,Harris, B. J. Lutein-fortified infant formula fed to healthy term infants: evaluation of growth effects and safety. Nutr J. 2010;9:22. | Independent variable
342 | Caplan, L. S.,Erwin, K.,Lense, E.,Hicks, J., Jr. The potential role of breast-feeding and other factors in helping to reduce early childhood caries. J Public Health Dent. 2008;68(4):238-41. | Study design, Independent variable
343 | Capozzi, L.,Russo, R.,Bertocco, F.,Ferrara, D.,Ferrara, M. Diet and iron deficiency in the first year of life: a retrospective study. Hematology. 2010;15(6):410-3. | Included for systematic reviews not completed
344 | Capozzi, L.,Russo, R.,Bertocco, F.,Ferrara, D.,Ferrara, M. Effect on haematological and anthropometric parameters of iron supplementation in the first 2 years of life. Risks and benefits. Hematology. 2011;16(5):261-4. | Independent variable
345 | Carberry, A. E.,Colditz, P. B.,Lingwood, B. E. Body composition from birth to 4.5 months in infants born to non-obese women. Pediatr Res. 2010;68(1):84-8. | Group size
346 | Carling, S. J.,Demment, M. M.,Kjolhede, C. L.,Olson, C. M. Breastfeeding duration and weight gain trajectory in infancy. Pediatrics. 2015;135(1):111-9. | Included for systematic reviews not completed
347 | Carlsen, K. H.,Larsen, S.,Bjerve, O.,Leegaard, J. Acute bronchiolitis: predisposing factors and characterization of infants at risk. Pediatr Pulmonol. 1987;3(3):153-60. | Group size
348 | Carlson, S. E.,DeVoe, P. W.,Barness, L. A. Effect of infant diets with different polyunsaturated to saturated fat ratios on circulating high-density lipoproteins. J Pediatr Gastroenterol Nutr. 1982;1(3):303-9. | Group size
349 | Carpenter, R.,McGarvey, C.,Mitchell, E. A.,Tappin, D. M.,Vennemann, M. M.,Smuk, M.,Carpenter, J. R. Bed sharing when parents do not smoke: Is there a risk of SIDS? An individual level analysis of five major case-control studies. BMJ Open. 2013;3(5). | Included for systematic reviews not completed
350 | Carr, A. Breastfeeding and the WIC program. Breastfeed Med. 2009;4 Suppl 1:S57-8. | Study design
351 | Carrascoza, K. C.,Possobon Rde, F.,Tomita, L. M.,Moraes, A. B. Consequences of bottle-feeding to the oral facial development of initially breastfed children. J Pediatr (Rio J). 2006;82(5):395-7. | Language
352 | Carroll, T. P. Substantially increasing breastfeeding: an accomplishment of the Alabama WIC Program. J Hum Lact. 1994;10(2):129-30. | Study design, Dependent variable
353 | Carson, C. G. Risk factors for developing atopic dermatitis. Dan Med J. 2013;60(7):B4687. | Independent variable
354 | Carter, C. S.,Porges, E. C. Parenthood, stress, and the brain. Biol Psychiatry. 2011;70(9):804-5. | Study design
355 | Carvalho, R.,Johnson, E.,Kozlosky, M.,Scheimann, A. O. Clinical profile of the overweight child in the new millennium. Clin Pediatr (Phila). 2008;47(5):476-82. | Study design, Health status
356 | Casazza, Krista,Fernandez, Jose R.,Allison, David B. Modest Protective Effects of Breast-feeding on Obesity: Is the Evidence Truly Supportive?. Nutrition Today. 2012;47(1):33-40 8p. | Study design
357 | Casiday, R. E.,Wright, C. M.,Panter-Brick, C.,Parkinson, K. N. Do early infant feeding patterns relate to breast-feeding continuation and weight gain? Data from a longitudinal cohort study. Eur J Clin Nutr. 2004;58(9):1290-6. | Included for systematic reviews not completed
358 | Caspi, A.,Williams, B.,Kim-Cohen, J.,Craig, I. W.,Milne, B. J.,Poulton, R.,Schalkwyk, L. C.,Taylor, A.,Werts, H.,Moffitt, T. E. Moderation of breastfeeding effects on the IQ by genetic variation in fatty acid metabolism. Proc Natl Acad Sci U S A. 2007;104(47):18860-5. | Included for systematic reviews not completed
359 | Cassimos, D. C.,Tsalkidis, A.,Tripsianis, G. A.,Stogiannidou, A.,Anthracopoulos, M.,Ktenidou-Kartali, S.,Aivazis, V.,Gardikis, S.,Chatzimichael, A. Asthma, lung function and sensitization in school children with a history of bronchiolitis. Pediatr Int. 2008;50(1):51-6. | Study design
360 | Castelo, P. M.,Gaviao, M. B.,Pereira, L. J.,Bonjardim, L. R. Maximal bite force, facial morphology and sucking habits in young children with functional posterior crossbite. J Appl Oral Sci. 2010;18(2):143-8. | Study design
361 | Castillo, C.,Atalah, E.,Riumallo, J.,Castro, R. Breast-feeding and the nutritional status of nursing children in Chile. Bull Pan Am Health Organ. 1996;30(2):125-33. | Study design
362 | Castro-Rodriguez, J. A.,Mallol, J.,Rodriguez, J.,Auger, F.,Andrade, R. Risk factors for X-ray pneumonia in the first year of life and its relation to wheezing: a longitudinal study in a socioeconomic disadvantaged population. Allergol Immunopathol (Madr). 2008;36(1):3-8. | Included for systematic reviews not completed
363 | Castro-Rodriguez, J. A.,Stern, D. A.,Halonen, M.,Wright, A. L.,Holberg, C. J.,Taussig, L. M.,Martinez, F. D. Relation between infantile colic and asthma/atopy: a prospective study in an unselected population. Pediatrics. 2001;108(4):878-82. | Dependent variable
364 | Catch-up growth following severe malnutrition. Nutr Rev. 1986;44(5):173-5. | Study design
365 | Cattaneo, A. Infant and young child feeding: solid facts. Breastfeed Rev. 2013;21(2):7-9. | Study design
366 | Cattaneo, A.,Ronfani, L.,Burmaz, T.,Quintero-Romero, S.,Macaluso, A.,Di Mario, S. Infant feeding and cost of health care: a cohort study. Acta Paediatr. 2006;95(5):540-6. | Dependent variable
367 | Cattaneo, A.,Timmer, A.,Bomestar, T.,Bua, J.,Kumar, S.,Tamburlini, G. Child nutrition in countries of the Commonwealth of Independent States: time to redirect strategies?. Public Health Nutr. 2008;11(12):1209-19. | Study design
368 | Caudri, D.,Savenije, O. E.,Smit, H. A.,Postma, D. S.,Koppelman, G. H.,Wijga, A. H.,Kerkhof, M.,Gehring, U.,Hoekstra, M. O.,Brunekreef, B.,de Jongste, J. C. Perinatal risk factors for wheezing phenotypes in the first 8 years of life. Clin Exp Allergy. 2013;43(12):1395-405. | Dependent variable
369 | Caulfield, L. E.,Bentley, M. E.,Ahmed, S. Is prolonged breastfeeding associated with malnutrition? Evidence from nineteen demographic and health surveys. Int J Epidemiol. 1996;25(4):693-703. | Study design
370 | Caulfield, L. E.,Bose, A.,Chandyo, R. K.,Nesamvuni, C.,de Moraes, M. L.,Turab, A.,Patil, C.,Mahfuz, M.,Ambikapathi, R.,Ahmed, T. Infant feeding practices, dietary adequacy, and micronutrient status measures in the MAL-ED study. Clin Infect Dis. 2014;59 Suppl 4:S248-54. | Study design
371 | Cavalcante e Silva, A.,Correia, L. L.,Campos, J. S.,Andrade, F. M.,Silveira, D. M.,Leite, A. J.,Rocha, H. A.,Machado, M. M.,Cunha, A. J. Reducing child mortality: the contribution of Ceara state, northeast of Brazil, on achieving the Millennium Development Goal 4 in Brazil. Matern Child Health J. 2015;19(4):700-6. | Study design
372 | Çelikkiran, S.,Bozkurt, H.,Coşkun, M. Denver developmental test findings and their relationship with sociodemographic variables in a large community sample of 0–4-year-old children. Noropsikiyatri Arsivi. 2015;52(2):180-184. | Study design
373 | Celikkiran, S.,Bozkurt, H.,Coskun, M. Denver developmental test findings and their relationship with sociodemographic variables in a large community sample of 0-4-year-old children. Noropsikiyatri Arsivi. 2015;52(2):180-4. | Study design
374 | Centers for Disease Control (CDC). Progress toward the 1990 objectives for improved nutrition. MMWR Morb Mortal Wkly Rep. 1988;37:475-9. | Study design
375 | Cerrato, P. L. Does milk cause juvenile diabetes?. Rn. 1993;56(1):69-72. | Study design
376 | Cerrato, P. L. Preventing food allergies. Rn. 1992;55(10):73-5. | Study design
377 | Cesar, J. A.,Victora, C. G.,Barros, F. C.,Santos, I. S.,Flores, J. A. Impact of breast feeding on admission for pneumonia during postneonatal period in Brazil: nested case-control study. BMJ. 1999;318(7194):1316-20. | Independent variable
378 | Chaffee, B. W.,Feldens, C. A.,Vitolo, M. R. Association of long-duration breastfeeding and dental caries estimated with marginal structural models. Ann Epidemiol. 2014;24(6):448-54. | Included for systematic reviews not completed
379 | Chaimay, B.,Ruagdaraganon, N.,Thinkhamrop, B.,Thinkhamrop, J. Association between infant feeding practices and first meaningful words at first year of life: a prospective cohort study of Thai children. Asia Pac J Public Health. 2015;27(2):NP1071-84. | Included for systematic reviews not completed
380 | Challacombe, D. N.,Mecrow, I. K.,Elliott, K.,Clarke, F. J.,Wheeler, E. E. Changing infant feeding practices and declining incidence of coeliac disease in West Somerset. Arch Dis Child. 1997;77(3):206-9. | Dependent variable
381 | Chaman, R.,Alami, A.,Emamian, M. H.,Naieni, K. H.,Mirmohammadkhani, M.,Ahmadnezhad, E.,Entezarmahdi, R.,Shati, M.,Shariati, M. Important risk factors of mortality among children aged 1-59 months in rural areas of Shahroud, Iran: A community-based nested case-control study. International Journal of Preventive Medicine. 2012;3(12):875-879. | Included for systematic reviews not completed
382 | Chan, G. M.,Leeper, L.,Book, L. S. Effects of soy formulas on mineral metabolism in term infants. Am J Dis Child. 1987;141(5):527-30. | Group size
383 | Chan, G. M.,Roberts, C. C.,Folland, D.,Jackson, R. Growth and bone mineralization of normal breast-fed infants and the effects of lactation on maternal bone mineral status. Am J Clin Nutr. 1982;36(3):438-43. | Group size
384 | Chandra, R. K. Five-year follow-up of high-risk infants with family history of allergy who were exclusively breast-fed or fed partial whey hydrolysate, soy, and conventional cow’s milk formulas. J Pediatr Gastroenterol Nutr. 1997;24(4):380-8. | Retracted
385 | Chandra, R. K.,Hamed, A. Cumulative incidence of atopic disorders in high risk infants fed whey hydrolysate, soy, and conventional cow milk formulas. Ann Allergy. 1991;67(2 Pt 1):129-32. | Independent variable
386 | Chandra, R. K.,Puri, S.,Cheema, P. S. Predictive value of cord blood IgE in the development of atopic disease and role of breast-feeding in its prevention. Clin Allergy. 1985;15(6):517-22. | Independent variable
387 | Chandra, R. K.,Puri, S.,Hamed, A. Influence of maternal diet during lactation and use of formula feeds on development of atopic eczema in high risk infants BMJ 1989 Oct 7;299(6704):896. BMJ (Clinical research ed.). 1989;299(6693):228-30. | Retracted
388 | Chandra, R. K.,Puri, S.,Suraiya, C.,Cheema, P. S. Influence of maternal food antigen avoidance during pregnancy and lactation on incidence of atopic eczema in infants. Clin Allergy. 1986;16(6):563-9. | Reliability questionable
389 | Chandran, L.,Gelfer, P. Breastfeeding: the essential principles. Pediatr Rev. 2006;27(11):409-17. | Study design
390 | Chan-Yeung, M.,Ferguson, A.,Watson, A.,Dimich, WArd H.,Dybuncio, A.,Rousseau, R.,Becker, A. Breastfeeding and risk of asthma and other allergic diseases at aged 7 years in a high-risk birth-cohort [Abstract]. American Thoracic Society 2005 International Conference; May 20-25; San Diego, California. 2005:[C49] [Poster: A85]. | Peer review
391 | Chan-Yeung, M.,Ferguson, A.,Watson, W.,Dimich-Ward, H.,Rousseau, R.,Lilley, M.,Dybuncio, A.,Becker, A. The Canadian Childhood Asthma Primary Prevention Study: outcomes at 7 years of age. J Allergy Clin Immunol. 2005;116(1):49-55. | Independent variable
392 | Chan-Yeung, M.,Manfreda, J.,Dimich-Ward, H.,Ferguson, A.,Watson, W.,Becker, A. A randomized controlled study on the effectiveness of a multifaceted intervention program in the primary prevention of asthma in high-risk infants. Arch Pediatr Adolesc Med. 2000;154(7):657-63. | Independent variable
393 | Chan-Yip, A.,Gray-Donald, K. Prevalence of iron deficiency among Chinese children aged 6 to 36 months in Montreal. CMAJ. 1987;136(4):373-8. | Independent variable
394 | Chaparro, C. M.,Neufeld, L. M.,Tena Alavez, G.,Eguia-Liz Cedillo, R.,Dewey, K. G. Effect of timing of umbilical cord clamping on iron status in Mexican infants: a randomised controlled trial. Lancet. 2006;367(9527):1997-2004. | Independent variable
395 | Chapman NL,Barnett DC. In defense of bottle-feeding. J Pract Nurs. 1982;32:24-7, 38. | Study design
396 | Chapman, D. J. Breastfeeding, brain imaging, and maternal behavior. J Hum Lact. 2011;27(3):304-5. | Study design, Dependent variable
397 | Chapman, D. J. Does breastfeeding result in smarter children? A closer look. J Hum Lact. 2013;29(4):444-5. | Study design
398 | Chapman, D. J. Exclusive breastfeeding through 6 months: infant intake and growth patterns. J Hum Lact. 2012;28(2):132-3. | Study design
399 | Chapman, D. J. Longer cumulative breastfeeding duration associated with improved bone strength. J Hum Lact. 2012;28(1):18-9. | Study design
400 | Chapman, D. J.,Morel, K.,Bermudez-Millan, A.,Young, S.,Damio, G.,Perez-Escamilla, R. Breastfeeding education and support trial for overweight and obese women: a randomized trial. Pediatrics. 2013;131(1):e162-70. | Independent variable, Dependent variable
401 | Chapman, D. J.,Nommsen-Rivers, L. Impact of maternal nutritional status on human milk quality and infant outcomes: an update on key nutrients. Adv Nutr. 2012;3(3):351-2. | Study design
402 | Chatzimichael, A.,Tsalkidis, A.,Cassimos, D.,Gardikis, S.,Tripsianis, G.,Deftereos, S.,Ktenidou-Kartali, S.,Tsanakas, I. The role of breastfeeding and passive smoking on the development of severe bronchiolitis in infants. Minerva Pediatr. 2007;59(3):199-206. | Health status
403 | Chavalittamrong, B.,Jirapinyo, P. The weight of Thai infants exclusively breast-fed and formula-fed from birth to four months. J Med Assoc Thai. 1987;70(5):247-51. | Included for systematic reviews not completed
404 | Chavez-Payan, P.,Grineski, S. E.,Collins, T. W. Early Life and Environmental Risk Factors Modify the Effect of Acculturation on Hispanic Children’s Asthma. Hisp Health Care Int. 2015;13(3):119-30. | Study design
405 | Chellakooty, M.,Juul, A.,Boisen, K. A.,Damgaard, I. N.,Kai, C. M.,Schmidt, I. M.,Petersen, J. H.,Skakkebæk, N. E.,Main, K. M. A prospective study of serum insulin-like growth factor I (IGF-I) and IGF-binding protein-3 in 942 healthy infants: Associations with birth weight, gender, growth velocity, and breastfeeding. Journal of Clinical Endocrinology and Metabolism. 2006;91(3):820-826. | Study design, Dependent variable
406 | Chen, A.,Rogan, W. J. Breastfeeding and the risk of postneonatal death in the United States. Pediatrics. 2004;113(5):e435-9. | Included for systematic reviews not completed
407 | Chen, B. Y.,Chan, C. C.,Han, Y. Y.,Wu, H. P.,Guo, Y. L. The risk factors and quality of life in children with allergic rhinitis in relation to seasonal attack patterns. Paediatr Perinat Epidemiol. 2012;26(2):146-55. | Study design
408 | Chen, C. F.,Hsu, M. C.,Shen, C. H.,Wang, C. L.,Chang, S. C.,Wu, K. G.,Wu, S. C.,Chen, S. J. Influence of breast-feeding on weight loss, jaundice, and waste elimination in neonates. Pediatr Neonatol. 2011;52(2):85-92. | Included for systematic reviews not completed
409 | Chen, C. J.,Wu, F. T.,Hsiung, C. A.,Chang, W. C.,Wu, H. S.,Wu, C. Y.,Lin, J. S.,Huang, F. C.,Huang, Y. C. Risk factors for salmonella gastroenteritis in children less than five years of age in Taiwan. Pediatr Infect Dis J. 2012;31(12):e239-43. | Included for systematic reviews not completed
410 | Chen, K.,Chai, L.,Li, H.,Zhang, Y.,Xie, H. M.,Shang, J.,Tian, W.,Yang, P.,Jiang, A. C.. Effect of bovine lactoferrin from iron-fortified formulas on morbidity of diarrhea and respiratory tract infections of weaned infants in a randomized controlled trial. Nutrition. 2015;#volume#(#issue#):#pages#. | Included for systematic reviews not completed
411 | Chen, M. Test a model of breast-feeding duration for Vietnamese mothers in Taiwan. Communicating Nursing Research. 2005;38:461-461 1p. | Study design
412 | Chen, S. M.,Du, J. W.,Jin, Y. M.,Qiu, L.,Du, Z. H.,Li, D. D.,Chen, H. Y.,Watanabe, C.,Umezaki, M. Risk Factors for Severe Hand-Foot-Mouth Disease in Children in Hainan, China, 2011-2012. Asia Pac J Public Health. 2015;27(7):715-22. | Independent variable, Dependent variable
413 | Chen, X. C.,Liu, D. S.,Fu, A. Z.,Yan, H. C.,Yin, T. A.,Jing, Y. S.,Xu, Q. M. A longitudinal study on infant growth during the first sixth months of life, in relation to the nutrition of the lactating mothers and to the breastmilk output. Prog Food Nutr Sci. 1989;13(2):113-37. | Independent variable
414 | Chen, Y. C.,Tsai, C. H.,Lee, Y. Gestational medication use, birth conditions, and early postnatal exposures for childhood asthma. Clin Dev Immunol. 2012;2012:913426. | Independent variable
415 | Chen, Y. Relationship between type of infant feeding and hospitalization for gastroenteritis in Shanghai infants. J Hum Lact. 1994;10(3):177-9. | Study design
416 | Chen, Y. Synergistic effect of passive smoking and artificial feeding on hospitalization for respiratory illness in early childhood. Chest. 1989;95(5):1004-7. | Study design
417 | Chen, Y.,Yu, S. Z.,Li, W. X. Artificial feeding and hospitalization in the first 18 months of life. Pediatrics. 1988;81(1):58-62. | Included for systematic reviews not completed
418 | Cheng, S.,Volgyi, E.,Tylavsky, F. A.,Lyytikainen, A.,Tormakangas, T.,Xu, L.,Cheng, S. M.,Kroger, H.,Alen, M.,Kujala, U. M. Trait-specific tracking and determinants of body composition: a 7-year follow-up study of pubertal growth in girls. BMC Med. 2009;7:5. | Included for systematic reviews not completed
419 | Cherian, A.,Lawande, R. V. Diarrhoeal disease in bottle fed children. J R Soc Health. 1987;107(2):62-3. | Country
420 | Chertok, I. R.,Raz, I.,Shoham, I.,Haddad, H.,Wiznitzer, A. Effects of early breastfeeding on neonatal glucose levels of term infants born to women with gestational diabetes. J Hum Nutr Diet. 2009;22(2):166-9. | Study design, Independent variable
421 | Chertok, I. R.,Shoham-Vardi, I. Infant hospitalization and breastfeeding post-caesarean section. Br J Nurs. 2008;17(12):786-91. | Dependent variable
422 | Chesney, R. W. Rickets: an old form for a new century. Pediatr Int. 2003;45(5):509-11. | Study design
423 | Chhonker, D.,Faridi, M. M.,Narang, M.,Sharma, S. B. Does type of feeding in infancy influence lipid profile in later life?. Indian J Pediatr. 2015;82(4):345-8. | Country
424 | Chiasson, M. A.,Scheinmann, R.,Hartel, D.,McLeod, N.,Sekhobo, J.,Edmunds, L. S.,Findley, S. Predictors of Obesity in a Cohort of Children Enrolled in WIC as Infants and Retained to 3 Years of Age. J Community Health. 2015. | Included for systematic reviews not completed
425 | Chierici, R.,Sawatzki, G.,Tamisari, L.,Volpato, S.,Vigi, V. Supplementation of an adapted formula with bovine lactoferrin. 2. Effects on serum iron, ferritin and zinc levels. Acta Paediatr. 1992;81(6-7):475-9. | Group size
426 | Chierici, R.,Sawatzki, G.,Thurl, S.,Tovar, K.,Vigi, V. Experimental milk formulae with reduced protein content and desialylated milk proteins: influence on the faecal flora and the growth of term newborn infants. Acta Paediatr. 1997;86(6):557-63. | Group size
427 | Chin, K. C.,Galea, P.,Goel, K. M. Changing pattern in infant feeding practices. Health Bull (Edinb). 1981;39(1):51-7. | Dependent variable
428 | Chiu, W. C.,Liao, H. F.,Chang, P. J.,Chen, P. C.,Chen, Y. C. Duration of breast feeding and risk of developmental delay in Taiwanese children: a nationwide birth cohort study. Paediatr Perinat Epidemiol. 2011;25(6):519-27. | Study design
429 | Chivers, P.,Hands, B.,Parker, H.,Bulsara, M.,Beilin, L. J.,Kendall, G. E.,Oddy, W. H. Body mass index, adiposity rebound and early feeding in a longitudinal cohort (Raine Study). Int J Obes (Lond). 2010;34(7):1169-76. | Included for systematic reviews not completed
430 | Chomtho, S. Breastfeeding to prevent double burden of malnutrition. Southeast Asian J Trop Med Public Health. 2014;45 Suppl 1:132-6. | Study design
431 | Chong, H. L.,Soo, T. L.,Rasat, R. Childhood obesity-prevalence among 7 and 8 year old primary school students in Kota Kinabalu. Medical Journal of Malaysia. 2012;67(2):147-150. | Study design
432 | Christopher, G. C. First food: the essential role of breastfeeding. Breastfeed Med. 2009;4 Suppl 1:S9-s10. | Study design
433 | Chu, L.,Retnakaran, R.,Zinman, B.,Hanley, A. J. G.,Hamilton, J. K. Impact of maternal physical activity and infant feeding practices on infant weight gain and adiposity. International Journal of Endocrinology. 2012;2012. | Independent variable
434 | Chuansumrit, A.,Arnutti, P.,Apivanich, S. Iron status of one-year-old infants in a well baby clinic. J Med Assoc Thai. 2002;85 Suppl 4:S1081-8. | Study design
435 | Chye, J. K.,Lim, C. T. Breastfeeding at 6 months and effects on infections. Singapore Med J. 1998;39(12):551-6. | Included for systematic reviews not completed
436 | Cilleruelo, M. L.,Fernandez-Fernandez, S.,Jimenez-Jimenez, J.,Rayo, A. I.,Larramendi, C. H. Prevalence and Natural History of Celiac Disease in a Cohort of at-Risk Children. J Pediatr Gastroenterol Nutr. 2015. | Study design
437 | Ciria-Martin, A.,Caravia-Bernardo, F.,Alvarez-Castello, M.,Insua-Arregui, C.,Tamargo-Barbeito, T. O.,Massip-Nicot, J. [Risk factors for recurrent upper airways infections in pre-school children]. Rev Alerg Mex. 2012;59(3):113-22. | Language
438 | Civelek, E.,Cakir, B.,Orhan, F.,Yuksel, H.,Boz, A. B.,Uner, A.,Sekerel, B. E. Risk factors for current wheezing and its phenotypes among elementary school children. Pediatr Pulmonol. 2011;46(2):166-74. | Study design
439 | Clark MJ. A case for breast feeding. Ky Nurse. 1984;32:14-5. | Study design
440 | Clark, K. M.,Castillo, M.,Calatroni, A.,Walter, T.,Cayazzo, M.,Pino, P.,Lozoff, B. Breast-feeding and mental and motor development at 51/2 years. Ambul Pediatr. 2006;6(2):65-71. | Independent variable
441 | Clark-Kellerman, M. J. A case for formula feeding. Ky Nurse. 1985;33(3):13-4. | Study design
442 | Clavano, N. R. Mode of feeding and its effect on infant mortality and morbidity. J Trop Pediatr. 1982;28(6):287-93. | Country
443 | Closa-Monasterolo, R.,Gispert-Llaurado, M.,Luque, V.,Ferre, N.,Rubio-Torrents, C.,Zaragoza-Jordana, M.,Escribano, J. Safety and efficacy of inulin and oligofructose supplementation in infant formula: results from a randomized clinical trial. Clin Nutr. 2013;32(6):918-27. | Independent variable, Dependent variable
444 | Close, C. Babies, bottles, and boobs. Br Med J (Clin Res Ed). 1987;295(6613):1666-7. | Study design
445 | Cochi, S. L.,Fleming, D. W.,Hightower, A. W.,Limpakarnjanarat, K.,Facklam, R. R.,Smith, J. D.,Sikes, R. K.,Broome, C. V. Primary invasive Haemophilus influenzae type b disease: a population-based assessment of risk factors. J Pediatr. 1986;108(6):887-96. | Dependent variable
446 | Cockburn, F. Neonatal brain and dietary lipids. Arch Dis Child Fetal Neonatal Ed. 1994;70(1):F1-2. | Study design
447 | Cogswell, J. J.,Mitchell, E. B.,Alexander, J. Parental smoking, breast feeding, and respiratory infection in development of allergic diseases. Arch Dis Child. 1987;62(4):338-44. | Independent variable
448 | Colchero, M. A.,Contreras-Loya, D.,Lopez-Gatell, H.,Gonzalez de Cosio, T. The costs of inadequate breastfeeding of infants in Mexico. Am J Clin Nutr. 2015;101(3):579-86. | Study design
449 | Collipp, P. J.,Kuo, B.,Castro-Magana, M.,Chen, S. Y.,Salvatore, S. Hair zinc levels in infants. Clin Pediatr (Phila). 1983;22(7):512-3. | Study design
450 | Cone, T. E., Jr. The nursing bottle caries syndrome. JAMA. 1981;245(22):2334. | Study design
451 | Connolly, C. Saving babies: child-saving and infant nutrition. Pediatr Nurs. 2005;31(4):309-11. | Study design
452 | Conover B. Exposures during pregnancy and lactation. Nebr Med J. 1992;77:65-7. | Study design
453 | Controversial breastfeeding study. Practising Midwife. 2001;4(5):6-6 1p. | Study design
454 | Coombes R. Bottling out over formula feed. Nurs Times. 1999;95:12-3. | Study design
455 | Coppi, S.,Iacoponi, F.,Fommei, C.,Strambi, M. Growth trend during the first six months of life in male infants with different type of feeding. Minerva Pediatr. 2013;65(1):51-9. | Included for systematic reviews not completed
456 | Cornish, R. P.,Tilling, K.,Boyd, A.,Davies, A.,Macleod, J. Using linked educational attainment data to reduce bias due to missing outcome data in estimates of the association between the duration of breastfeeding and IQ at 15 years. Int J Epidemiol. 2015;44(3):937-45. | Included for systematic reviews not completed
457 | Corrao, G.,Tragnone, A.,Caprilli, R.,Trallori, G.,Papi, C.,Andreoli, A.,Di Paolo, M.,Riegler, G.,Rigo, G. P.,Ferrau, O.,Mansi, C.,Ingrosso, M.,Valpiani, D. Risk of inflammatory bowel disease attributable to smoking, oral contraception and breastfeeding in Italy: a nationwide case-control study. Cooperative Investigators of the Italian Group for the Study of the Colon and the Rectum (GISC). Int J Epidemiol. 1998;27(3):397-404. | Independent variable
458 | Correa-Faria, P.,Martins-Junior, P. A.,Vieira-Andrade, R. G.,Marques, L. S.,Ramos-Jorge, M. L. Perinatal factors associated with developmental defects of enamel in primary teeth: a case-control study. Braz Oral Res. 2013;27(4):363-8. | Included for systematic reviews not completed
459 | Corvalan, C.,Kain, J.,Weisstaub, G.,Uauy, R. Impact of growth patterns and early diet on obesity and cardiovascular risk factors in young children from developing countries. Proc Nutr Soc. 2009;68(3):327-37. | Study design
460 | Corvalan, C.,Uauy, R.,Stein, A. D.,Kain, J.,Martorell, R. Effect of growth on cardiometabolic status at 4 y of age. Am J Clin Nutr. 2009;90(3):547-55. | Study design
461 | Counsilman, J. J.,Chan, S. Y.,Haiyon, H.,Rahim, N. A.,Salim, R.,Tai, T. Y.,Tan, M. L.,Zainy, Z.,Viegas, O. Breast feeding among poor Singaporeans. J Trop Pediatr. 1986;32(6):310-2. | Dependent variable
462 | Counsilman, J. J.,Chua, S.,Viegas, O. Breast feeding among well-to-do Singaporeans. J Trop Pediatr. 1986;32(6):313-6. | Dependent variable
463 | Couper, J. J.,Beresford, S.,Hirte, C.,Baghurst, P. A.,Pollard, A.,Tait, B. D.,Harrison, L. C.,Colman, P. G. Weight gain in early life predicts risk of islet autoimmunity in children with a first-degree relative with type 1 diabetes. Diabetes Care. 2009;32(1):94-9. | Dependent variable
464 | Couper, J. J.,Steele, C.,Beresford, S.,Powell, T.,McCaul, K.,Pollard, A.,Gellert, S.,Tait, B.,Harrison, L. C.,Colman, P. G. Lack of association between duration of breast-feeding or introduction of cow’s milk and development of islet autoimmunity. Diabetes. 1999;48(11):2145-9. | Dependent variable
465 | Cowden, M. Infant feeding. Midwives Chron. 1982;95(1136):319-20. | Study design
466 | Cow’s milk allergy in the first year of life. An Italian Collaborative Study. Acta Paediatr Scand Suppl. 1988;348:1-14. | Study design, Health status
467 | Crestani, A. H.,Souza, A. P.,Beltrami, L.,Moraes, A. B. Analysis of the association among types of breastfeeding, presence of child development risk, socioeconomic and obstetric variables. J Soc Bras Fonoaudiol. 2012;24(3):205-10. | Study design, Dependent variable
468 | Crewe, E.,Murphy, A. M. Further studies on neonatal rotavirus infections. Med J Aust. 1980;1(2):61-3. | Study design, Dependent variable
469 | Crossland, D. S.,Richmond, S.,Hudson, M.,Smith, K.,Abu-Harb, M. Weight change in the term baby in the first 2 weeks of life. Acta Paediatr. 2008;97(4):425-9. | Included for systematic reviews not completed
470 | Crouch, A. A.,Seow, W. K.,Whitman, L. M.,Thong, Y. H. Effect of human milk and infant milk formulae on adherence of Giardia intestinalis. Trans R Soc Trop Med Hyg. 1991;85(5):617-9. | Independent variable, Non-human
471 | Crouch, S.,Lightfoot, T.,Simpson, J.,Smith, A.,Ansell, P.,Roman, E. Infectious illness in children subsequently diagnosed with acute lymphoblastic leukemia: modeling the trends from birth to diagnosis. Am J Epidemiol. 2012;176(5):402-8. | Independent variable
472 | Crow, D. R. Baby bottle tooth decay prevention--a new program for the Texas Department of Health. Tex Dent J. 1992;109(8):141. | Study design
473 | Croxatto, H. B.,Diaz, S.,Peralta, O.,Juez, G.,Herreros, C.,Casado, M. E.,Salvatierra, A. M.,Miranda, P.,Duran, E. Fertility regulation in nursing women: IV. Long-term influence of a low-dose combined oral contraceptive initiated at day 30 postpartum upon lactation and infant growth. Contraception. 1983;27(1):13-25. | Independent variable
474 | Crume, T. L.,Bahr, T. M.,Mayer-Davis, E. J.,Hamman, R. F.,Scherzinger, A. L.,Stamm, E.,Dabelea, D. Selective protection against extremes in childhood body size, abdominal fat deposition, and fat patterning in breastfed children. Arch Pediatr Adolesc Med. 2012;166(5):437-43. | Study design
475 | Crume, T. L.,Ogden, L. G.,Mayer-Davis, E. J.,Hamman, R. F.,Norris, J. M.,Bischoff, K. J.,McDuffie, R.,Dabelea, D. The impact of neonatal breast-feeding on growth trajectories of youth exposed and unexposed to diabetes in utero: the EPOCH Study. Int J Obes (Lond). 2012;36(4):529-34. | Included for systematic reviews not completed
476 | Crume, T. L.,Ogden, L.,Maligie, M.,Sheffield, S.,Bischoff, K. J.,McDuffie, R.,Daniels, S.,Hamman, R. F.,Norris, J. M.,Dabelea, D. Long-term impact of neonatal breastfeeding on childhood adiposity and fat distribution among children exposed to diabetes in utero. Diabetes Care. 2011;34(3):641-5. | Study design, Independent variable
477 | Cruz, M. L.,Wong, W. W.,Mimouni, F.,Hachey, D. L.,Setchell, K. D.,Klein, P. D.,Tsang, R. C. Effects of infant nutrition on cholesterol synthesis rates. Pediatr Res. 1994;35(2):135-40. | Group size
478 | Cuhaci Çakir, B.,Beyazova, U.,Kemalo?lu, Y. K.,Özkan, S.,Gündüz, B.,Özdek, A. Effectiveness of pandemic influenza A/H1N1 vaccine for prevention of otitis media in children. European journal of pediatrics. 2012;171(11):1667-71. | Independent variable
479 | Cullinan, T. R.,Saunders, D. I. Prediction of infant hospital admission risk. Arch Dis Child. 1983;58(6):423-7. | Study design, Independent variable
480 | Cunningham, A. S. Breast-feeding and health. J Pediatr. 1987;110(4):658-9. | Study design
481 | Current issues in feeding the normal infant. Pediatrics. 1985;75(1 Pt 2):135-215. | Study design
482 | Curtis, J. A.,Kooh, S. W.,Fraser, D.,Greenberg, M. L. Nutritional rickets in vegetarian children. Can Med Assoc J. 1983;128(2):150-2. | Study design
483 | Cushing, A. H.,Anderson, L. Diarrhea in breast-fed and non-breast-fed infants. Pediatrics. 1982;70(6):921-5. | Group size
484 | Cushing, A. H.,Samet, J. M.,Lambert, W. E.,Skipper, B. J.,Hunt, W. C.,Young, S. A.,McLaren, L. C. Breastfeeding reduces risk of respiratory illness in infants. Am J Epidemiol. 1998;147(9):863-70. | Included for systematic reviews not completed
485 | Cusick, S. E.,Mei, Z.,Cogswell, M. E. Continuing anemia prevention strategies are needed throughout early childhood in low-income preschool children. J Pediatr. 2007;150(4):422-8, 428 e1-2. | Included for systematic reviews not completed
486 | Cutting, W. A. Cholera and breastfeeding. Trop Doct. 2002;32(1):57-8. | Study design
487 | Dada, J. H. Nutrition and type 1 diabetes: can diet reduce risk?. Today’s Dietitian. 2010;12(8):36-39 4p. | Study design
488 | Dadhich, J. P.,Agarwal, R. K. Mainstreaming early and exclusive breastfeeding for improving child survival. Indian Pediatr. 2009;46(1):11-7. | Study design, Country
489 | Daga, S. R. Reduction in neonatal mortality by simple interventions. J Biosoc Sci Suppl. 1989;10:127-36. | Country
490 | Daga, S. R.,Daga, A. S. Reduction in neonatal mortality with simple interventions. J Trop Pediatr. 1989;35(4):191-6. | Study design, Country
491 | Dagan, R.,Pridan, H. Relationship of breast feeding versus bottle feeding with emergency room visits and hospitalization for infectious diseases. Eur J Pediatr. 1982;139(3):192-4. | Included for systematic reviews not completed
492 | Dahlquist, G.,Mustonen, L. Analysis of 20 years of prospective registration of childhood onset diabetes time trends and birth cohort effects. Swedish Childhood Diabetes Study Group. Acta Paediatr. 2000;89(10):1231-7. | Study design, Independent variable
493 | Dahlquist, G.,Savilahti, E.,Landin-Olsson, M. An increased level of antibodies to β-lactoglobulin is a risk determinant for early-onset Type 1 (insulin-dependent) diabetes mellitus independent of islet cell antibodies and early introduction of cow’s milk. Diabetologia. 1992;35(10):980-984. | Independent variable, Dependent variable
494 | Dalmeijer, G. W.,Wijga, A. H.,Gehring, U.,Renders, C. M.,Koppelman, G. H.,Smit, H. A.,van Rossem, L. Fatty acid composition in breastfeeding and school performance in children aged 12 years. Eur J Nutr. 2015. | Included for systematic reviews not completed
495 | Daly, K. A.,Rich, S. S.,Levine, S.,Margolis, R. H.,Le, C. T.,Lindgren, B.,Giebink, G. S. The family study of otitis media: design and disease and risk factor profiles. Genet Epidemiol. 1996;13(5):451-68. | Study design, Health status
496 | Damore, D.,Mansbach, J. M.,Clark, S.,Ramundo, M.,Camargo, C. A., Jr. Prospective multicenter bronchiolitis study: predicting intensive care unit admissions. Acad Emerg Med. 2008;15(10):887-94. | Study design
497 | Daniels, L. A.,Mallan, K. M.,Nicholson, J. M.,Battistutta, D.,Magarey, A. Outcomes of an early feeding practices intervention to prevent childhood obesity. Pediatrics. 2013;132(1):e109-e118. | Independent variable
498 | Darmstadt, G. L.,Munar, W. Behavior change and community participation: Assessing causal pathways affecting neonatal mortality. JAMA - Journal of the American Medical Association. 2013;310(9):969-70. | Study design, Country
499 | Darnall, B. D.,Schatman, M. E. Protecting the infant from unknown risks. Pain Med. 2015;16(4):631-2. | Study design
500 | DaVanzo, J.,Habicht, J. P. Infant mortality decline in Malaysia, 1946-1975: the roles of changes in variables and changes in the structure of relationships. Demography. 1986;23(2):143-60. | Study design
501 | Davanzo, R.,Cannioto, Z.,Ronfani, L.,Monasta, L.,Demarini, S. Breastfeeding and neonatal weight loss in healthy term infants. J Hum Lact. 2013;29(1):45-53. | Independent variable
502 | David, C. B.,David, P. H.,el Lozy, M. Determinants of breastfeeding duration and nutrition in a transition society. J Trop Pediatr. 1983;29(1):45-9. | Country
503 | Davidson, R.,Roberts, S. E.,Wotton, C. J.,Goldacre, M. J. Influence of maternal and perinatal factors on subsequent hospitalisation for asthma in children: evidence from the Oxford record linkage study. BMC Pulm Med. 2010;10:14. | Independent variable
504 | Davis, D. W.,Bell, P. A. Infant feeding practices and occlusal outcomes: a longitudinal study. J Can Dent Assoc. 1991;57(7):593-4. | Included for systematic reviews not completed
505 | Davis, J. N.,Gunderson, E. P.,Gyllenhammer, L. E.,Goran, M. I. Impact of gestational diabetes mellitus on pubertal changes in adiposity and metabolic profiles in Latino offspring. J Pediatr. 2013;162(4):741-5. | Study design, Independent variable
506 | Davis, J. N.,Whaley, S. E.,Goran, M. I. Effects of breastfeeding and low sugar-sweetened beverage intake on obesity prevalence in Hispanic toddlers. Am J Clin Nutr. 2012;95(1):3-8. | Study design
507 | Davis, J. Well advised: a journey to breastfeeding success. Pract Midwife. 2014;17(8):34, 36-8. | Study design
508 | de Beer, M.,Vrijkotte, T. G.,Fall, C. H.,van Eijsden, M.,Osmond, C.,Gemke, R. J. Associations of infant feeding and timing of linear growth and relative weight gain during early life with childhood body composition. Int J Obes (Lond). 2015;39(4):586-92. | Included for systematic reviews not completed
509 | de Boer, R. A topic in 10 questions: assessing common dietary deficiencies. J Fam Health Care. 2011;21(6):28-9. | Study design
510 | de Bruin, N. C.,Degenhart, H. J.,Gal, S.,Westerterp, K. R.,Stijnen, T.,Visser, H. K. Energy utilization and growth in breast-fed and formula-fed infants measured prospectively during the first year of life. Am J Clin Nutr. 1998;67(5):885-96. | Group size
511 | de Fátima Buco Busto Moreno, Patrícia,Trombini Schmidt, Kayna. BREAST-FEEDING AND FACTORS RELATED TO EARLY WEANING. Cogitare Enfermagem. 2014;19(3):531-537 7p. | Dependent variable
512 | de Freitas, C. L.,Romani, S.,Amigo, H. Breast-feeding and malnutrition in rural areas of northeast Brazil. Bull Pan Am Health Organ. 1986;20(2):138-46. | Study design, Dependent variable
513 | de Hoog, M. L.,van Eijsden, M.,Stronks, K.,Gemke, R. J.,Vrijkotte, T. G. The role of infant feeding practices in the explanation for ethnic differences in infant growth: the Amsterdam Born Children and their Development study. Br J Nutr. 2011;106(10):1592-601. | Included for systematic reviews not completed
514 | de Jong, C.,Kikkert, H. K.,Fidler, V.,Hadders-Algra, M. Effects of long-chain polyunsaturated fatty acid supplementation of infant formula on cognition and behaviour at 9 years of age. Dev Med Child Neurol. 2012;54(12):1102-8. | Included for systematic reviews not completed
515 | de Jong, C.,Kikkert, H. K.,Fidler, V.,Hadders-Algra, M. The Groningen LCPUFA study: no effect of postnatal long-chain polyunsaturated fatty acids in healthy term infants on neurological condition at 9 years. Br J Nutr. 2010;104(4):566-72. | Included for systematic reviews not completed
516 | De Kroon, M. L.,Renders, C. M.,Buskermolen, M. P.,Van Wouwe, J. P.,van Buuren, S.,Hirasing, R. A. The Terneuzen Birth Cohort. Longer exclusive breastfeeding duration is associated with leaner body mass and a healthier diet in young adulthood. BMC Pediatr. 2011;11:33. | Independent variable
517 | de la Hunty, A. The EU Childhood Obesity Project. Nutrition Bulletin. 2009;34(4):403-406 4p. | Study design, Independent variable
518 | de Looy, A. E. Infant nutrition. Nursing (Lond). 1986;3(12):446-9. | Study design
519 | De Lucia Rolfe, E.,Modi, N.,Uthaya, S.,Hughes, I. A.,Dunger, D. B.,Acerini, C.,Stolk, R. P.,Ong, K. K. Ultrasound estimates of visceral and subcutaneous-abdominal adipose tissues in infancy. J Obes. 2013;2013:951954. | Included for systematic reviews not completed
520 | de Melo, M. C. N.,Taddei, J. A. A. C.,Diniz-Santos, D. R.,Vieira, C.,Carneiro, N. B.,Melo, R. F.,Silva, L. R. Incidence of diarrhea in children living in urban slums in Salvador, Brazil. Brazilian Journal of Infectious Diseases. 2008;12(1):89-93. | Independent variable
521 | de Oliveira Bezerra, Joana Lidyanne,De Vasconcelos, Maria Gorete Lucena,Pereira Linhares, Francisca Márcia,Javorski, Marly,Leal, Luciana Pedrosa. Maternal perception of their children’s body image in exclusive breastfeeding. Acta Paulista de Enfermagem. 2014;27(4):293-299 7p. | Study design
522 | de Oliveira, D. M.,Dahan, P.,Ferreira, D. F.,de Oliveira, L. F.,de Paula, L. I.,de Figueiredo, A. A.,de Bessa, J., Jr.,Bastos Netto, J. M. Association between exclusive maternal breastfeeding during the first 4 months of life and primary enuresis. J Pediatr Urol. 2015. | Dependent variable
523 | de Rooy, L.,Hawdon, J. Nutritional factors that affect the postnatal metabolic adaptation of full-term small- and large-for-gestational-age infants. Pediatrics. 2002;109(3):E42. | Dependent variable
524 | De Souza, A. C.,Petersont, K. E.,Cufino, E.,do Amaral, M. I.,Gardner, J. Underlying and proximate determinants of diarrhoea-specific infant mortality rates among municipalities in the state of Ceara, north-east Brazil: an ecological study. J Biosoc Sci. 2001;33(2):227-44. | Study design, Independent variable
525 | Deacon C. Breastfeeding. Are we just bottling out?. Nurs Times. 2001;97:26-7. | Study design
526 | Dedoussis, G. V.,Yannakoulia, M.,Timpson, N. J.,Manios, Y.,Kanoni, S.,Scott, R. A.,Papoutsakis, C.,Deloukas, P.,Pitsiladis, Y. P.,Davey-Smith, G.,Hirschhorn, J. N.,Lyon, H. N. Does a short breastfeeding period protect from FTO-induced adiposity in children?. Int J Pediatr Obes. 2011;6(2-2):e326-35. | Study design
527 | Deliu, M.,Belgrave, D.,Simpson, A.,Murray, C. S.,Kerry, G.,Custovic, A. Impact of rhinitis on asthma severity in school-age children. Allergy. 2014;69(11):1515-21. | Dependent variable
528 | Dell, S.,To, T. Breastfeeding and asthma in young children: findings from a population-based study. Arch Pediatr Adolesc Med. 2001;155(11):1261-5. | Study design
529 | Demir, A. U.,Celikel, S.,Karakaya, G.,Kalyoncu, A. F. Asthma and allergic diseases in school children from 1992 to 2007 with incidence data. J Asthma. 2010;47(10):1128-35. | Study design
530 | Demment, M. M.,Haas, J. D.,Olson, C. M. Changes in family income status and the development of overweight and obesity from 2 to 15 years: a longitudinal study. BMC Public Health. 2014;14:417. | Included for systematic reviews not completed
531 | Demmers, T. A.,Jones, P. J.,Wang, Y.,Krug, S.,Creutzinger, V.,Heubi, J. E. Effects of early cholesterol intake on cholesterol biosynthesis and plasma lipids among infants until 18 months of age. Pediatrics. 2005;115(6):1594-601. | Group size
532 | Dennehy, P. H.,Cortese, M. M.,Begue, R. E.,Jaeger, J. L.,Roberts, N. E.,Zhang, R.,Rhodes, P.,Gentsch, J.,Ward, R.,Bernstein, D. I.,Vitek, C.,Bresee, J. S.,Staat, M. A. A case-control study to determine risk factors for hospitalization for rotavirus gastroenteritis in U.S. children. Pediatr Infect Dis J. 2006;25(12):1123-31. | Independent variable
533 | Der, G.,Batty, G. D.,Deary, I. J. Effect of breast feeding on intelligence in children: Prospective study, sibling pairs analysis, and meta-analysis. British Medical Journal. 2006;333(7575):945-948. | Included for systematic reviews not completed
534 | Derkson, G. D.,Ponti, P. Nursing bottle syndrome; prevalence and etiology in a non-fluoridated city. J Can Dent Assoc. 1982;48(6):389-93. | Study design
535 | Deshpande, W. Exclusive breastfeeding for the first six months. Community Pract. 2008;81(5):34-6. | Study design
536 | Dewailly, E.,Ayotte, P.,Bruneau, S.,Gingras, S.,Belles-Isles, M.,Roy, R. Susceptibility to infections and immune status in Inuit infants exposed to organochlorines. Environ Health Perspect. 2000;108(3):205-11. | Included for systematic reviews not completed
537 | Dewey, K. G. Complementary feeding and breastfeeding. Pediatrics. 2000;106(5):1301. | Study design
538 | Dewey, K. G.,Hawck, M. G.,Brown, K. H.,Lartey, A.,Cohen, R. J.,Peerson, J. M. Infant weight-for-length is positively associated with subsequent linear growth across four different populations. Matern Child Nutr. 2005;1(1):11-20. | Independent variable
539 | Dewey, K. G.,Heinig, M. J.,Nommsen, L. A.,Lonnerdal, B. Adequacy of energy intake among breast-fed infants in the DARLING study: relationships to growth velocity, morbidity, and activity levels. Davis Area Research on Lactation, Infant Nutrition and Growth. J Pediatr. 1991;119(4):538-47. | Independent variable
540 | Dewey, K. G.,Heinig, M. J.,Nommsen, L. A.,Peerson, J. M.,Lonnerdal, B. Breast-fed infants are leaner than formula-fed infants at 1 y of age: the DARLING study. Am J Clin Nutr. 1993;57(2):140-5. | Independent variable
541 | Dewey, K. G.,Heinig, M. J.,Nommsen, L. A.,Peerson, J. M.,Lonnerdal, B. Growth of breast-fed and formula-fed infants from 0 to 18 months: the DARLING Study. Pediatrics. 1992;89(6 Pt 1):1035-41. | Independent variable
542 | Dewey, K. G.,Heinig, M. J.,Nommsen-Rivers, L. A. Differences in morbidity between breast-fed and formula-fed infants. J Pediatr. 1995;126(5 Pt 1):696-702. | Independent variable
543 | Dewey, K. G.,Nommsen-Rivers, L. A.,Heinig, M. J.,Cohen, R. J. Risk factors for suboptimal infant breastfeeding behavior, delayed onset of lactation, and excess neonatal weight loss. Pediatrics. 2003;112(3 Pt 1):607-19. | Independent variable
544 | Dewey, K. G.,Peerson, J. M.,Brown, K. H.,Krebs, N. F.,Michaelsen, K. F.,Persson, L. A.,Salmenpera, L.,Whitehead, R. G.,Yeung, D. L. Growth of breast-fed infants deviates from current reference data: a pooled analysis of US, Canadian, and European data sets. World Health Organization Working Group on Infant Growth. Pediatrics. 1995;96(3 Pt 1):495-503. | Study design
545 | Dewey, K. G.,Peerson, J. M.,Heinig, M. J.,Nommsen, L. A.,Lonnerdal, B.,Lopez de Romana, G.,de Kanashiro, H. C.,Black, R. E.,Brown, K. H. Growth patterns of breast-fed infants in affluent (United States) and poor (Peru) communities: implications for timing of complementary feeding. Am J Clin Nutr. 1992;56(6):1012-8. | Study design, Independent variable
546 | Dharmage, S. C.,Rajapaksa, L. C.,Fernando, D. N. Risk factors of acute lower respiratory tract infections in children under five years of age. Southeast Asian J Trop Med Public Health. 1996;27(1):107-10. | Health status
547 | Diarrhoeal disease control (CDD) and acute respiratory infections (ARI). Combined CDD/ARI/breast-feeding survey, 1992. Wkly Epidemiol Rec. 1993;68(17):120-2. | Study design, Independent variable
548 | Diarrhoeal Disease Control (CDD) Programme. Wkly Epidemiol Rec. 1993;68:345-9. | Study design
549 | Diaz, S.,Herreros, C.,Aravena, R.,Casado, M. E.,Reyes, M. V.,Schiappacasse, V. Breast-feeding duration and growth of fully breast-fed infants in a poor urban Chilean population. Am J Clin Nutr. 1995;62(2):371-6. | Independent variable
550 | Diaz, S.,Rodriguez, G.,Marshall, G.,del Pino, G.,Casado, M. E.,Miranda, P.,Schiappacasse, V.,Croxatto, H. B. Breastfeeding pattern and the duration of lactational amenorrhea in urban Chilean women. Contraception. 1988;38(1):37-51. | Dependent variable
551 | Diesel, J. C.,Eckhardt, C. L.,Day, N. L.,Brooks, M. M.,Arslanian, S. A.,Bodnar, L. M. Is gestational weight gain associated with offspring obesity at 36 months?. Pediatr Obes. 2015;10(4):305-10. | Independent variable
552 | Dietary and other risk factors of ulcerative colitis. A case-control study in Japan. Epidemiology Group of the Research Committee of Inflammatory Bowel Disease in Japan. J Clin Gastroenterol. 1994;19(2):166-71. | Independent variable
553 | Dini, E. L.,Holt, R. D.,Bedi, R. Caries and its association with infant feeding and oral health-related behaviours in 3-4-year-old Brazilian children. Community Dent Oral Epidemiol. 2000;28(4):241-8. | Study design
554 | Dinsmore, J.,Williams, E.,McCarthy, H.,Coghlan, D. A pilot study to explore factors affecting faltering growth in children. Journal of Human Nutrition & Dietetics. 2011;24(3):280-281 2p. | No full text
555 | Disantis, K. I.,Collins, B. N.,Fisher, J. O.,Davey, A. Do infants fed directly from the breast have improved appetite regulation and slower growth during early childhood compared with infants fed from a bottle?. Int J Behav Nutr Phys Act. 2011;8:89. | Included for systematic reviews not completed
556 | Dixon, D. L.,Griggs, K. M.,Forsyth, K. D.,Bersten, A. D. Lower interleukin-8 levels in airway aspirates from breastfed infants with acute bronchiolitis. Pediatr Allergy Immunol. 2010;21(4 Pt 2):e691-6. | Dependent variable
557 | Djalalinia, S.,Qorbani, M.,Heshmat, R.,Motlagh, M. E.,Ardalan, G.,Bazyar, N.,Taheri, M.,Asayesh, H.,Kelishadi, R. Association of Breast Feeding and Birth Weight with Anthropometric Measures and Blood Pressure in Children and Adolescents: The CASPIAN-IV Study. Pediatr Neonatol. 2015;56(5):324-33. | Study design
558 | Does breastfeeding increase risk of early childhood caries? J Can Dent Assoc. 2013;79:d123. | Peer review
559 | Does breastfeeding prevent obesity?..and what about dairy foods?. Child Health Alert. 2004;22:3-4. | Study design
560 | Dogaru, C. M.,Strippoli, M. P.,Spycher, B. D.,Frey, U.,Beardsmore, C. S.,Silverman, M.,Kuehni, C. E. Breastfeeding and lung function at school age: does maternal asthma modify the effect?. Am J Respir Crit Care Med. 2012;185(8):874-80. | Dependent variable
561 | Dogruel, D.,Bingol, G.,Altintas, D. U.,Yilmaz, M.,Kendirli, S. G. Prevalence of and risk factors for atopic dermatitis: A birth cohort study of infants in southeast Turkey. Allergol Immunopathol (Madr). 2015. | Independent variable
562 | Domellof, E.,Timby, N.,Domellof, M.,Lonnerdal, B.,Hernell, O. Formula feeding supplemented with milk fat globule membranes improves cognitive score in term infants at 12 months. Developmental medicine and child neurology. 2013;55:50. | Study design
563 | Dondi, A.,Tripodi, S.,Panetta, V.,Asero, R.,Businco, A. D.,Bianchi, A.,Carlucci, A.,Ricci, G.,Bellini, F.,Maiello, N.,del Giudice, M. M.,Frediani, T.,Sodano, S.,Dello Iacono, I.,Macri, F.,Massaccesi, V.,Caffarelli, C.,Rinaldi, L.,Patria, M. F.,Varin, E.,Peroni, D.,Chinellato, I.,Chini, L.,Moschese, V.,Lucarelli, S.,Bernardini, R.,Pingitore, G.,Pelosi, U.,Tosca, M.,Paravati, F.,La Grutta, S.,Meglio, P.,Calvani, M.,Plebani, M.,Matricardi, P. M. Pollen-induced allergic rhinitis in 1360 Italian children: comorbidities and determinants of severity. Pediatr Allergy Immunol. 2013;24(8):742-51. | Study design
564 | Dong, G. H.,Qian, Z. M.,Liu, M. M.,Wang, D.,Ren, W. H.,Bawa, S.,Fu, J.,Wang, J.,Lewis, R.,Zelicoff, A.,Simckes, M.,Trevathan, E. Breastfeeding as a modifier of the respiratory effects of air pollution in children. Epidemiology. 2013;24(3):387-94. | Study design
565 | Dong, G. H.,Qian, Z. M.,Trevathan, E.,Zeng, X. W.,Vaughn, M. G.,Wang, J.,Zhao, Y.,Liu, Y. Q.,Ren, W. H.,Qin, X. D. Air pollution associated hypertension and increased blood pressure may be reduced by breastfeeding in Chinese children: the Seven Northeastern Cities Chinese Children’s Study. Int J Cardiol. 2014;176(3):956-61. | Study design
566 | Donma, M. M.,Donma, O. Infant feeding and growth: a study on Turkish infants from birth to 6 months. Pediatr Int. 1999;41(5):542-8. | Independent variable
567 | Donma, M. M.,Donma, O. The influence of feeding patterns on head circumference among Turkish infants during the first 6 months of life. Brain Dev. 1997;19(6):393-7. | Included for systematic reviews not completed
568 | Donohue, L. Baby Friendly Hospitals in China. Aust J Adv Nurs. 1994;12(2):7. | Study design
569 | Doran, E. Breast is best for lightweights. Nurs Mirror. 1983;156(12):46-7. | Health status
570 | Dorea, J. G. Zinc in urban infants and children from Brasilia. Arch Latinoam Nutr. 1997;47(2 Suppl 1):39-40. | Study design
571 | Dorea, J. G.,Marques, R. C.,Isejima, C. Neurodevelopment of Amazonian infants: antenatal and postnatal exposure to methyl- and ethylmercury. J Biomed Biotechnol. 2012;2012:132876. | Study design, Independent variable
572 | Dotan, I.,Alper, A.,Rachmilewitz, D.,Israeli, E.,Odes, S.,Chermesh, I.,Naftali, T.,Fraser, G.,Shitrit, A. B.,Peles, V.,Reif, S. Maternal inflammatory bowel disease has short and long-term effects on the health of their offspring: a multicenter study in Israel. J Crohns Colitis. 2013;7(7):542-50. | Independent variable, Dependent variable
573 | Douglas, R. M.,Woodward, A.,Miles, H.,Buetow, S.,Morris, D. A prospective study of proneness to acute respiratory illness in the first two years of life. Int J Epidemiol. 1994;23(4):818-26. | Dependent variable
574 | Doumid Borges Pretto, A.,Correa Kaufmann, C.,Ferreira Dutra, G.,Pinto Albernaz, E. Prevalence of factors related to the bone mass formation of children from a cohort in Southern Brazil. Nutr Hosp. 2015;31(3):1122-8. | Independent variable
575 | Draaisma, E.,Garcia-Marcos, L.,Mallol, J.,Sole, D.,Perez-Fernandez, V.,Brand, P. L. A multinational study to compare prevalence of atopic dermatitis in the first year of life. Pediatr Allergy Immunol. 2015;26(4):359-66. | Study design, Dependent variable
576 | Drewett, R. F.,Amatayakul, K. Energy intake, appetite and body mass in infancy. Early Hum Dev. 1999;56(1):75-82. | Independent variable
577 | Drewett, R.,Amatayakul, K.,Chiowanich, P.,Tansuhaj, A.,Ruckphaopunt, S.,Wongsawasdii, L.,Baum, D.,Imong, S.,Jackson, D.,Woolridge, M. The Chiang Mai lactation project: study design and implementation. Paediatr Perinat Epidemiol. 1991;5(3):347-60. | Independent variable
578 | Drover, J.,Hoffman, D. R.,Castaneda, Y. S.,Morale, S. E.,Birch, E. E. Three randomized controlled trials of early long-chain polyunsaturated Fatty Acid supplementation on means-end problem solving in 9-month-olds. Child Dev. 2009;80(5):1376-84. | Independent variable
579 | Du, Y.,Ellert, U.,Lampert, T.,Mensink, G. B.,Schlaud, M. Association of breastfeeding and exposure to maternal smoking during pregnancy with children’s general health status later in childhood. Breastfeed Med. 2012;7(6):504-13. | Study design, Dependent variable
580 | Dubakiene, R.,Rudzeviciene, O.,Butiene, I.,Sezaite, I.,Petronyte, M.,Vaicekauskaite, D.,Zvirbliene, A. Studies on early allergic sensitization in the Lithuanian birth cohort. ScientificWorldJournal. 2012;2012:909524. | Independent variable
581 | Dube, K.,Schwartz, J.,Mueller, M. J.,Kalhoff, H.,Kersting, M. Iron intake and iron status in breastfed infants during the first year of life. Clin Nutr. 2010;29(6):773-8. | Group size
582 | Dubois, L.,Girard, M. Early determinants of overweight at 4.5 years in a population-based longitudinal study. Int J Obes (Lond). 2006;30(4):610-7. | Included for systematic reviews not completed
583 | Duffy, L. C.,Byers, T. E.,Riepenhoff-Talty, M.,La Scolea, L. J.,Zielezny, M.,Ogra, P. L. The effects of infant feeding on rotavirus-induced gastroenteritis: a prospective study. Am J Public Health. 1986;76(3):259-63. | Included for systematic reviews not completed
584 | Duffy, L. C.,Faden, H.,Wasielewski, R.,Wolf, J.,Krystofik, D. Exclusive breastfeeding protects against bacterial colonization and day care exposure to otitis media. Pediatrics. 1997;100(4):E7. | Included for systematic reviews not completed
585 | Duffy, L. C.,Riepenhoff-Talty, M.,Byers, T. E.,La Scolea, L. J.,Zielezny, M. A.,Dryja, D. M.,Ogra, P. L. Modulation of rotavirus enteritis during breast-feeding. Implications on alterations in the intestinal bacterial flora. Am J Dis Child. 1986;140(11):1164-8. | Included for systematic reviews not completed
586 | Dugdale, A. E. Infant feeding, growth and mortality: a 20-year study of an Australian Aboriginal community. Med J Aust. 1980;2(7):380-5. | Included for systematic reviews not completed
587 | Duijts, L.,Jaddoe, V. W.,Hofman, A.,Moll, H. A. Prolonged and exclusive breastfeeding reduces the risk of infectious diseases in infancy. Pediatrics. 2010;126(1):e18-25. | Included for systematic reviews not completed
588 | Dumrongwongsiri, O.,Suthutvoravut, U.,Chatvutinun, S.,Phoonlabdacha, P.,Sangcakul, A.,Siripinyanond, A.,Thiengmanee, U.,Chongviriyaphan, N. Maternal zinc status is associated with breast milk zinc concentration and zinc status in breastfed infants aged 4-6 months. Asia Pac J Clin Nutr. 2015;24(2):273-80. | Study design
589 | Duncan, B.,Ey, J.,Holberg, C. J.,Wright, A. L.,Martinez, F. D.,Taussig, L. M. Exclusive breast-feeding for at least 4 months protects against otitis media. Pediatrics. 1993;91(5):867-72. | Included for systematic reviews not completed
590 | Dunlop, A. L.,Reichrtova, E.,Palcovicova, L.,Ciznar, P.,Adamcakova-Dodd, A.,Smith, S. J.,McNabb, S. J. Environmental and dietary risk factors for infantile atopic eczema among a Slovak birth cohort. Pediatr Allergy Immunol. 2006;17(2):103-11. | Study design
591 | Dunne, A. Early infant nutrition: the importance of getting it right. Br J Nurs. 2012;21(7):390. | Study design
592 | Dunne, A. Nutrition in infancy: achieving nutrition needs for new mothers and children. Br J Community Nurs. 2012;Suppl:S22. | Study design
593 | Dunson, D. B.,Chulada, P.,Arbes, S. J., Jr. Bayesian modeling of time-varying and waning exposure effects. Biometrics. 2003;59(1):83-91. | Study design
594 | Durmu, B.,Ay, L.,Duijts, L.,Moll, H. A.,Hokken-Koelega, A. C. S.,Raat, H.,Hofman, A.,Steegers, E. A. P.,Jaddoe, V. W. V. Infant diet and subcutaneous fat mass in early childhood: The Generation R Study. European Journal of Clinical Nutrition. 2012;66(2):253-260. | Included for systematic reviews not completed
595 | Durmus, B.,Ay, L.,Hokken-Koelega, A. C.,Raat, H.,Hofman, A.,Steegers, E. A.,Jaddoe, V. W. Maternal smoking during pregnancy and subcutaneous fat mass in early childhood. The Generation R Study. Eur J Epidemiol. 2011;26(4):295-304. | Independent variable
596 | Durmus, B.,Heppe, D. H.,Gishti, O.,Manniesing, R.,Abrahamse-Berkeveld, M.,van der Beek, E. M.,Hofman, A.,Duijts, L.,Gaillard, R.,Jaddoe, V. W. General and abdominal fat outcomes in school-age children associated with infant breastfeeding patterns. Am J Clin Nutr. 2014;99(6):1351-8. | Included for systematic reviews not completed
597 | Durmus, B.,van Rossem, L.,Duijts, L.,Arends, L. R.,Raat, H.,Moll, H. A.,Hofman, A.,Steegers, E. A.,Jaddoe, V. W. Breast-feeding and growth in children until the age of 3 years: the Generation R Study. Br J Nutr. 2011;105(11):1704-11. | Included for systematic reviews not completed
598 | Dutta, P.,Lahiri, M.,Sen, D.,Pal, S. C. Prospective hospital based study on persistent diarrhoea. Gut. 1991;32(7):787-90. | Country
599 | Dwyer, T.,Ponsonby, A. L. SIDS epidemiology and incidence. Pediatr Ann. 1995;24(7):350-2, 354-6. | Study design
600 | Eaton-Evans, J.,Dugdale, A. E. Effects of feeding and social factors on diarrhoea and vomiting in infants. Arch Dis Child. 1987;62(5):445-8. | Included for systematic reviews not completed
601 | Ebina, S.,Kashiwakura, I. Relationship between feeding modes and infant weight gain in the first month of life. Exp Ther Med. 2013;5(1):28-32. | Included for systematic reviews not completed
602 | Eckhardt, C. L.,Rivera, J.,Adair, L. S.,Martorell, R. Full breast-feeding for at least four months has differential effects on growth before and after six months of age among children in a Mexican community. J Nutr. 2001;131(9):2304-9. | Independent variable
603 | Ecord, J. S. Critical connections. Study finds full breastfeeding for 6 months boosts infant’s resistance to respiratory illnesses. Advances in Neonatal Care (Elsevier Science). 2003;3(1):2-2 1p. | Study design
604 | Effects of breast-feeding: new results from a large randomised trial. Journal of Family Health Care. 2008;18(1):34-34 1p. | Study design
605 | Eglinton, T. W.,Roberts, R.,Pearson, J.,Barclay, M.,Merriman, T. R.,Frizelle, F. A.,Gearry, R. B. Clinical and genetic risk factors for perianal Crohn’s disease in a population-based cohort. Am J Gastroenterol. 2012;107(4):589-96. | Dependent variable
606 | Eickmann, S. H.,de Lira, P. I.,Lima Mde, C.,Coutinho, S. B.,Teixeira Mde, L.,Ashworth, A. Breast feeding and mental and motor development at 12 months in a low-income population in northeast Brazil. Paediatr Perinat Epidemiol. 2007;21(2):129-37. | Independent variable
607 | Eidelman, A. I. Breastfeeding mitigates a disaster. Breastfeed Med. 2013;8(3):344-5. | Study design
608 | Eiger, M. S.,Rausen, A. R.,Silverio, J. Breast-vs. bottle-feeding. A study of morbidity in upper middle class infants. Clin Pediatr (Phila). 1984;23(9):492-5. | Group size
609 | Ejlerskov, K. T.,Christensen, L. B.,Ritz, C.,Jensen, S. M.,Molgaard, C.,Michaelsen, K. F. The impact of early growth patterns and infant feeding on body composition at 3 years of age. Br J Nutr. 2015;114(2):316-27. | Included for systematic reviews not completed
610 | Ek, J.,Magnus, E. Plasma and red cell folate values and folate requirements in formula-fed term infants. J Pediatr. 1982;100(5):738-44. | Group size
611 | Ekstrom, A.,Abrahamsson, H.,Eriksson, R. M.,Martensson, B. L. Women’s use of nipple shields-Their influence on breastfeeding duration after a process-oriented education for health professionals. Breastfeed Med. 2014;9(9):458-66. | Independent variable
612 | Elborn, G.,Kerr, M. M. Acceptability trial of “Milumil” artificial milk for infant feeding. Midwives Chron. 1982;95(1133):210-1. | Independent variable
613 | Eldeirawi, K.,McConnell, R.,Furner, S.,Freels, S.,Stayner, L.,Hernandez, E.,Amoruso, L.,Torres, S.,Persky, V. W. Associations of doctor-diagnosed asthma with immigration status, age at immigration, and length of residence in the United States in a sample of Mexican American School Children in Chicago. J Asthma. 2009;46(8):796-802. | Study design
614 | El-Gilany, A. H.,El-Wehady, A. Maternal work and infant health in Al-Hassa, Saudi Arabia. Paediatrics ME. 2007;12(4):100-105. | Study design
615 | Elidrissy, A. T.,Sedrani, S. H.,Lawson, D. E. Vitamin D deficiency in mothers of rachitic infants. Calcif Tissue Int. 1984;36(3):266-8. | Study design, Independent variable
616 | Elliott, K. G.,Kjolhede, C. L.,Gournis, E.,Rasmussen, K. M. Duration of breastfeeding associated with obesity during adolescence. Obes Res. 1997;5(6):538-41. | Included for systematic reviews not completed
617 | Elliott, L.,Henderson, J.,Northstone, K.,Chiu, G. Y.,Dunson, D.,London, S. J. Prospective study of breast-feeding in relation to wheeze, atopy, and bronchial hyperresponsiveness in the Avon Longitudinal Study of Parents and Children (ALSPAC). J Allergy Clin Immunol. 2008;122(1):49-54, 54 e1-3. | Dependent variable
618 | Elwood, P. C.,Pickering, J.,Gallacher, J. E.,Hughes, J.,Davies, D. Long term effect of breast feeding: cognitive function in the Caerphilly cohort. J Epidemiol Community Health. 2005;59(2):130-3. | Included for systematic reviews not completed
619 | Emamghorashi, F.,Heydari, S. T. Growth of infants in relation to type of feeding in Jahrom, Islamic Republic of Iran. East Mediterr Health J. 2007;13(4):846-54. | Included for systematic reviews not completed
620 | Emilsson, L.,Magnus, M. C.,Stordal, K. Perinatal risk factors for development of celiac disease in children, based on the prospective Norwegian Mother and Child Cohort Study. Clin Gastroenterol Hepatol. 2015;13(5):921-7. | Independent variable
621 | Emmett, P. M.,Jones, L. R. Diet and growth in infancy: relationship to socioeconomic background and to health and development in the Avon Longitudinal Study of Parents and Children. Nutr Rev. 2014;72(8):483-506. | Study design
622 | Emond, A.,Drewett, R.,Blair, P.,Emmett, P. Postnatal factors associated with failure to thrive in term infants in the Avon Longitudinal Study of Parents and Children. Arch Dis Child. 2007;92(2):115-9. | Included for systematic reviews not completed
623 | Emond, A.,Pollock, J.,Da Costa, N.,Maranhao, T.,Macedo, A. The effectiveness of community-based interventions to improve maternal and infant health in the Northeast of Brazil. Rev Panam Salud Publica. 2002;12(2):101-10. | Study design, Independent variable
624 | Endesfelder, D.,zu Castell, W.,Ardissone, A.,Davis-Richardson, A. G.,Achenbach, P.,Hagen, M.,Pflueger, M.,Gano, K. A.,Fagen, J. R.,Drew, J. C.,Brown, C. T.,Kolaczkowski, B.,Atkinson, M.,Schatz, D.,Bonifacio, E.,Triplett, E. W.,Ziegler, A. G. Compromised gut microbiota networks in children with anti-islet cell autoimmunity. Diabetes. 2014;63(6):2006-14. | Independent variable, Dependent variable
625 | Engel, J.,Anteunis, L.,Volovics, A.,Hendriks, J.,Marres, E. Risk factors of otitis media with effusion during infancy. Int J Pediatr Otorhinolaryngol. 1999;48(3):239-49. | Included for systematic reviews not completed
626 | Eriksen, H. L.,Kesmodel, U. S.,Underbjerg, M.,Kilburn, T. R.,Bertrand, J.,Mortensen, E. L. Predictors of intelligence at the age of 5: family, pregnancy and birth characteristics, postnatal influences, and postnatal growth. PLoS One. 2013;8(11):e79200. | Study design
627 | Eriksson, J.,Forsen, T.,Osmond, C.,Barker, D. Obesity from cradle to grave. Int J Obes Relat Metab Disord. 2003;27(6):722-7. | Included for systematic reviews not completed
628 | Eriksson, M.,Forsgren, M.,Sjoberg, S.,von Sydow, M.,Wolontis, S. Respiratory syncytial virus infection in young hospitalized children. Identification of risk patients and prevention of nosocomial spread by rapid diagnosis. Acta Paediatr Scand. 1983;72(1):47-51. | Study design, Health status
629 | Ernst, E. Probiotics may prevent atopic disease. Focus on Alternative & Complementary Therapies. 2001;6(3):204-205 2p. | Study design
630 | Eronat, N.,Eden, E. A comparative study of some influencing factors of rampant or nursing caries in preschool children. J Clin Pediatr Dent. 1992;16(4):275-9. | Study design, Independent variable
631 | Escribano, J.,Luque, V.,Ferre, N.,Mendez-Riera, G.,Koletzko, B.,Grote, V.,Demmelmair, H.,Bluck, L.,Wright, A.,Closa-Monasterolo, R. Effect of protein intake and weight gain velocity on body fat mass at 6 months of age: the EU Childhood Obesity Programme. Int J Obes (Lond). 2012;36(4):548-53. | Included for systematic reviews not completed
632 | Eskenazi, B.,Marks, A. R.,Bradman, A.,Fenster, L.,Johnson, C.,Barr, D. B.,Jewell, N. P. In utero exposure to dichlorodiphenyltrichloroethane (DDT) and dichlorodiphenyldichloroethylene (DDE) and neurodevelopment among young Mexican American children. Pediatrics. 2006;118(1):233-41. | Study design
633 | Esmail, A.,Lambert, P. C.,Jones, D. R.,Mitchell, E. A. Prevalence of risk factors for sudden infant death syndrome in south east England before the 1991 national ‘Back to Sleep’ health education campaign. J Public Health Med. 1995;17(3):282-9. | Study design
634 | Estevez-Gonzalez, M. D.,Santana Del Pino, A.,Henriquez-Sanchez, P.,Pena-Quintana, L.,Saavedra-Santana, P. Breastfeeding during the first six months of life, adiposity rebound and overweight/obesity at eight years of age. Int J Obes (Lond). 2015. | Included for systematic reviews not completed
635 | Ethelberg, S.,Olesen, B.,Neimann, J.,Schiellerup, P.,Helms, M.,Jensen, C.,Böttiger, B.,Olsen, K. E. P.,Scheutz, F.,Gerner-Smidt, P.,Mølbak, K. Risk factors for diarrhea among children in an industrialized country. Epidemiology. 2006;17(1):24-30. | Independent variable
636 | Etiler, N.,Velipasaoglu, S.,Aktekin, M. Incidence of acute respiratory infections and the relationship with some factors in infancy in Antalya, Turkey. Pediatr Int. 2002;44(1):64-9. | Included for systematic reviews not completed
637 | Etiler, N.,Velipasaoglu, S.,Aktekin, M. Risk factors for overall and persistent diarrhoea in infancy in Antalya, Turkey: a cohort study. Public Health. 2004;118(1):62-9. | Included for systematic reviews not completed
638 | Evenhouse, E.,Reilly, S. Improved estimates of the benefits of breastfeeding using sibling comparisons to reduce selection bias. Health Serv Res. 2005;40(6 Pt 1):1781-802. | Study design
639 | Exclusive breast feeding is protective against asthma and atopy in children. Bmj. 1999;319(7213):D. | Study design
640 | Exl, B. M.,Deland, U.,Secretin, M. C.,Preysch, U.,Wall, M.,Shmerling, D. H. Improved general health status in an unselected infant population following an allergen-reduced dietary intervention programme: The ZUFF-STUDY-PROGRAMME - Part II: Infant growth and health status to age 6 months. European Journal of Nutrition. 2000;39(4):145-156. | Study design, Independent variable, Dependent variable
641 | Exl, B. M.,Deland, U.,Wall, M.,Preysch, U.,Secretin, M. C.,Shmerling, D. H. Zug-Frauenfeld nutritional survey (‘Zuff Study’): Allergen-reduced nutrition in a normal infant population and its health-related effects: Results at the age of six months. Nutrition research (New York, N.Y.). 1998;18(8):1443-62. | Study design
642 | Fagrell, T. G.,Ludvigsson, J.,Ullbro, C.,Lundin, S. A.,Koch, G. Aetiology of severe demarcated enamel opacities--an evaluation based on prospective medical and social data from 17,000 children. Swed Dent J. 2011;35(2):57-67. | Included for systematic reviews not completed
643 | Fall, C. H.,Borja, J. B.,Osmond, C.,Richter, L.,Bhargava, S. K.,Martorell, R.,Stein, A. D.,Barros, F. C.,Victora, C. G. Infant-feeding patterns and cardiovascular risk factors in young adulthood: data from five cohorts in low- and middle-income countries. Int J Epidemiol. 2011;40(1):47-62. | Study design
644 | Fallot, M. E.,Boyd, J. L., 3rd,Oski, F. A. Breast-feeding reduces incidence of hospital admissions for infection in infants. Pediatrics. 1980;65(6):1121-4. | Study design
645 | Falth-Magnusson, K.,Franzen, L.,Jansson, G.,Laurin, P.,Stenhammar, L. Infant feeding history shows distinct differences between Swedish celiac and reference children. Pediatr Allergy Immunol. 1996;7(1):1-5. | Dependent variable
646 | Falth-Magnusson, K.,Kjellman, N. I. Development of atopic disease in babies whose mothers were receiving exclusion diet during pregnancy--a randomized study. J Allergy Clin Immunol. 1987;80(6):868-75. | Independent variable
647 | Farham, B. Rethink formula feeding. South African medical journal. 2006;96(10):1054. | Study design
648 | Farooqi, I. S.,Hopkin, J. M. Early childhood infection and atopic disorder. Thorax. 1998;53(11):927-32. | Independent variable
649 | Farris, R. P.,Frank, G. C.,Webber, L. S.,Srinivasan, S. R.,Berenson, G. S. Influence of milk source on serum lipids and lipoproteins during the first year of life, Bogalusa heart study. Am J Clin Nutr. 1982;35(1):42-9. | Independent variable
650 | Fawcett JN. Feeding from birth to 18 months. Nursing (Lond). 1981:956-8. | Study design
651 | Fawzi, W. W.,Forman, M. R.,Levy, A.,Graubard, B. I.,Naggan, L.,Berendes, H. W. Maternal anthropometry and infant feeding practices in Israel in relation to growth in infancy: the North African Infant Feeding Study. Am J Clin Nutr. 1997;65(6):1731-7. | Included for systematic reviews not completed
652 | Fawzi, W. W.,Herrera, M. G.,Nestel, P.,el Amin, A.,Mohamed, K. A. A longitudinal study of prolonged breastfeeding in relation to child undernutrition. Int J Epidemiol. 1998;27(2):255-60. | Country
653 | Feig, D. S.,Lipscombe, L. L.,Tomlinson, G.,Blumer, I. Breastfeeding predicts the risk of childhood obesity in a multi-ethnic cohort of women with diabetes. J Matern Fetal Neonatal Med. 2011;24(3):511-5. | Study design
654 | Feigal, R. J. Common oral diseases of children. Pediatr Ann. 1985;14(2):133-8. | Study design
655 | Fein, S. B.,Grummer-Strawn, L. M.,Raju, T. N. Infant feeding and care practices in the United States: results from the Infant Feeding Practices Study II. Pediatrics. 2008;122 Suppl 2:S25-7. | Study design
656 | Feldens, C. A.,Giugliani, E. R.,Duncan, B. B.,Drachler Mde, L.,Vitolo, M. R. Long-term effectiveness of a nutritional program in reducing early childhood caries: a randomized trial. Community Dent Oral Epidemiol. 2010;38(4):324-32. | Included for systematic reviews not completed
657 | Feldens, C. A.,Giugliani, E. R.,Vigo, A.,Vitolo, M. R. Early feeding practices and severe early childhood caries in four-year-old children from southern Brazil: a birth cohort study. Caries Res. 2010;44(5):445-52. | Included for systematic reviews not completed
658 | Feldens, C. A.,Kramer, P. F.,Feldens, E. G.,Pacheco, L. M.,Vitolo, M. R. Socioeconomic, behavioral, and anthropometric risk factors for traumatic dental injuries in childhood: a cohort study. Int J Paediatr Dent. 2014;24(3):234-43. | Dependent variable
659 | Feldens, C. A.,Vitolo, M. R.,Drachler Mde, L. A randomized trial of the effectiveness of home visits in preventing early childhood caries. Community Dent Oral Epidemiol. 2007;35(3):215-23. | Included for systematic reviews not completed
660 | Fenger-Gron J, Fenger-Gron M, Blunck CH, Schonemann-Rigel H, Wielandt HB. Low breastfeeding rates and body mass index in Danish children of women with gestational diabetes mellitus. International Breastfeeding Journal. 2015;10(1):1-12 12p. | Included for systematic reviews not completed
661 | Ferguson, A. E.,Tappin, D. M.,Girdwood, R. W. A.,Kennedy, R.,Cockburn, F. Breast feeding in Scotland. British Medical Journal. 1994;308(6932):824-825. | Study design, Dependent variable
662 | Fergusson, D. M.,Beautrais, A. L.,Silva, P. A. Breast-feeding and cognitive development in the first seven years of life. Soc Sci Med. 1982;16(19):1705-8. | Included for systematic reviews not completed
663 | Fergusson, D. M.,Horwood, L. J. Early solid food diet and eczema in childhood: a 10-year longitudinal study. Pediatr Allergy Immunol. 1994;5(6 Suppl):44-7. | Independent variable
664 | Fergusson, D. M.,Horwood, L. J.,Beautrais, A. L.,Shannon, F. T.,Taylor, B. Eczema and infant diet. Clin Allergy. 1981;11(4):325-31. | Independent variable
665 | Fergusson, D. M.,Horwood, L. J.,Shannon, F. T. Asthma and infant diet. Arch Dis Child. 1983;58(1):48-51. | Independent variable
666 | Fergusson, D. M.,Horwood, L. J.,Shannon, F. T. Breastfeeding and subsequent social adjustment in six- to eight-year-old children. J Child Psychol Psychiatry. 1987;28(3):379-86. | Included for systematic reviews not completed
667 | Fergusson, D. M.,Horwood, L. J.,Shannon, F. T. Risk factors in childhood eczema. J Epidemiol Community Health. 1982;36(2):118-22. | Independent variable
668 | Fergusson, D. M.,Horwood, L. J.,Shannon, F. T.,Taylor, B. Breast-feeding, gastrointestinal and lower respiratory illness in the first two years. Aust Paediatr J. 1981;17(3):191-5. | Included for systematic reviews not completed
669 | Fergusson, D. M.,McLeod, G. F.,Horwood, L. J. Breast feeding, infant growth, and body mass index at 30 and 35 years. Paediatr Perinat Epidemiol. 2014;28(6):545-52. | Included for systematic reviews not completed
670 | Fergusson, D. M.,Woodward, L. J. Breast feeding and later psychosocial adjustment. Paediatr Perinat Epidemiol. 1999;13(2):144-57. | Included for systematic reviews not completed
671 | Ferris, A. G.,Laus, M. J.,Hosmer, D. W.,Beal, V. A. The effect of diet on weight gain in infancy. Am J Clin Nutr. 1980;33(12):2635-42. | Independent variable
672 | Fewtrell, M. S.,Kennedy, K.,Murgatroyd, P. R.,Williams, J. E.,Chomtho, S.,Lucas, A. Breast-feeding and formula feeding in healthy term infants and bone health at age 10 years. Br J Nutr. 2013;110(6):1061-7. | Group size
673 | Field, C. J.,Van Aerde, J. E.,Robinson, L. E.,Clandinin, M. T. Feeding a formula supplemented with long chain polyunsaturated fatty acids modifies the “ex vivo” cytokine responses to food proteins in infants at low risk for allergy. Pediatr Res. 2008;64(4):411-7. | Group size
674 | Field, S. S. Interaction of genes and nutritional factors in the etiology of autism and attention deficit/hyperactivity disorders: a case control study. Med Hypotheses. 2014;82(6):654-61. | Included for systematic reviews not completed
675 | Fildes, A.,van Jaarsveld, C. H.,Llewellyn, C.,Wardle, J.,Fisher, A. Parental control over feeding in infancy. Influence of infant weight, appetite and feeding method. Appetite. 2015;91:101-6. | Dependent variable
676 | Fildes, V. Weaning: on the bottle again. Nurs Mirror. 1980;151(24):18-21. | Study design
677 | Findeisen, M.,Vennemann, M.,Brinkmann, B.,Ortmann, C.,Rose, I.,Kopcke, W.,Jorch, G.,Bajanowski, T. German study on sudden infant death (GeSID): design, epidemiological and pathological profile. Int J Legal Med. 2004;118(3):163-9. | Included for systematic reviews not completed
678 | Firer, M. A.,Hosking, C. S.,Hill, D. J. Effect of antigen load on development of milk antibodies in infants allergic to milk. Br Med J (Clin Res Ed). 1981;283(6293):693-6. | Group size
679 | Fisher C. Breastfeeding. Two. Feeding the relationship. Nurs Times. 1985;81:51. | Study design
680 | Fisher SE,Markowitz J,Lifshitz F. Food intolerance in childhood. Compr Ther. 1984;10:5-11. | Study design
681 | Fisk, C. M.,Crozier, S. R.,Inskip, H. M.,Godfrey, K. M.,Cooper, C.,Roberts, G. C.,Robinson, S. M. Breastfeeding and reported morbidity during infancy: findings from the Southampton Women’s Survey. Matern Child Nutr. 2011;7(1):61-70. | Included for systematic reviews not completed
682 | Fitzgerald, S.,Kearney, M.,Mahony, M.,O’Halloran, E. T.,Barry, R. G. Gastroenteritis 1972-1978. Ir Med J. 1982;75(5):155-7. | Study design
683 | Flaherman, V. J.,Bokser, S.,Newman, T. B. First-day newborn weight loss predicts in-hospital weight nadir for breastfeeding infants. Breastfeed Med. 2010;5(4):165-8. | Independent variable
684 | Flaherman, V. J.,Fuentes-Afflick, E. Social and public health perspectives of promotion of breastfeeding. JAMA Pediatr. 2014;168(10):877-8. | Study design
685 | Flaherman, V. J.,Kuzniewicz, M. W.,Li, S.,Walsh, E.,McCulloch, C. E.,Newman, T. B. First-day weight loss predicts eventual weight nadir for breastfeeding newborns. Arch Dis Child Fetal Neonatal Ed. 2013;98(6):F488-92. | Independent variable, Dependent variable
686 | Flaherman, V.,Aby, J.,Burgos, A.,Lee, K.,Cabana, M.,Newman, T. Randomized Trial of Early Limited Formula To Reduce Formula Use at 1 Week and Promote Breastfeeding at 3 Months in Infants with High Early Weight Loss. Pediatric Academic Societies Annual Meeting. 2012. | Peer review
687 | Fleddermann, M.,Demmelmair, H.,Grote, V.,Nikolic, T.,Koletzko, B. A protein reduced, alpha-lactalbumin and LC-PUFA containing infant formula enables an adequate growth in infants and influences the energetic efficiency for growth: A randomized controlled trial. Clinical nutrition (Edinburgh, Scotland). 2013;32:S16. | Peer review
688 | Fleming, P. J.,Blair, P. S.,Bacon, C.,Bensley, D.,Smith, I.,Taylor, E.,Berry, J.,Golding, J.,Tripp, J. Environment of infants during sleep and risk of the sudden infant death syndrome: results of 1993-5 case-control study for confidential inquiry into stillbirths and deaths in infancy. Confidential Enquiry into Stillbirths and Deaths Regional Coordinators and Researchers. BMJ. 1996;313(7051):191-5. | Included for systematic reviews not completed
689 | Fleming, P. J.,Blair, P. S.,Ward Platt, M.,Tripp, J.,Smith, I. J. Sudden infant death syndrome and social deprivation: assessing epidemiological factors after post-matching for deprivation. Paediatr Perinat Epidemiol. 2003;17(3):272-80. | Included for systematic reviews not completed
690 | Fleming, T. Breast is best to avoid obesity: study. Pharmacy News. 2008:4-4 1p. | Study design
691 | Flohr, C.,Nagel, G.,Weinmayr, G.,Kleiner, A.,Strachan, D. P.,Williams, H. C. Lack of evidence for a protective effect of prolonged breastfeeding on childhood eczema: lessons from the International Study of Asthma and Allergies in Childhood (ISAAC) Phase Two. Br J Dermatol. 2011;165(6):1280-9. | Study design
692 | Flohr, C.,Perkin, M.,Logan, K.,Marrs, T.,Radulovic, S.,Campbell, L. E.,Maccallum, S. F.,McLean, W. H.,Lack, G. Atopic dermatitis and disease severity are the main risk factors for food sensitization in exclusively breastfed infants. J Invest Dermatol. 2014;134(2):345-50. | Independent variable
693 | Flores, M. S.,Fairchok, M. P. The relationship of breastfeeding to antimicrobial exposure in the first year of life. Clin Pediatr (Phila). 2004;43(7):631-6. | Dependent variable
694 | Flores, M.,Pasquel, M. R.,Maulen, I.,Rivera, J. Exclusive breastfeeding in 3 rural localities in Mexico. J Hum Lact. 2005;21(3):276-83. | Study design, Independent variable
695 | Floret, D.,Lina, B.,Pinchinat, S.,Billaud, G.,Ait-Belghiti, F.,Largeron, N.,Bellemin, B.,Trang, C. N.,Fau, C.,Gaspard, C.,Mamoux, V.,Marcelon, L. Epidemiology and burden of rotavirus diarrhea in day care centers in Lyon, France. Eur J Pediatr. 2006;165(12):905-6. | Study design, Independent variable
696 | Florey, C. D.,Leech, A. M.,Blackhall, A. Infant feeding and mental and motor development at 18 months of age in first born singletons. Int J Epidemiol. 1995;24 Suppl 1:S21-6. | Included for systematic reviews not completed
697 | Florez, C. E.,Hogan, D. P. Women’s status and infant mortality in rural Colombia. Soc Biol. 1990;37(3-4):188-203. | Study design, Independent variable
698 | Fogaca, H. R.,Marson, F. A.,Toro, A. A.,Sole, D.,Ribeiro, J. D. Epidemiological aspects of and risk factors for wheezing in the first year of life. J Bras Pneumol. 2014;40(6):617-25. | Study design
699 | Foley, S.,Quinn, S.,Jones, G. Tracking of bone mass from childhood to adolescence and factors that predict deviation from tracking. Bone. 2009;44(5):752-7. | Included for systematic reviews not completed
700 | Folic, N.,Folic, M.,Markovic, S.,Andjelkovic, M.,Jankovic, S. Risk factors for the development of metabolic syndrome in obese children and adolescents. Srp Arh Celok Lek. 2015;143(3-4):146-52. | Study design
701 | Fomon, S. J. Assessment of growth of formula-fed infants: evolutionary considerations. Pediatrics. 2004;113(2):389-93. | Study design
702 | Fomon, S. J. Factors influencing food consumption in the human infant. Int J Obes. 1980;4(4):348-50. | Study design
703 | Fomon, S. J.,Rogers, R. R.,Ziegler, E. E.,Nelson, S. E.,Thomas, L. N. Indices of fatness and serum cholesterol at age eight years in relation to feeding and growth during early infancy. Pediatr Res. 1984;18(12):1233-8. | Independent variable
704 | Fomon, S. J.,Ziegler, E. E.,Nelson, S. E. Erythrocyte incorporation of ingested 58Fe by 56-day-old breast-fed and formula-fed infants. Pediatr Res. 1993;33(6):573-6. | Group size
705 | Fomon, S. J.,Ziegler, E. E.,Nelson, S. E.,Rogers, R. R.,Frantz, J. A. Infant formula with protein-energy ratio of 1.7 g/100 kcal is adequate but may not be safe. J Pediatr Gastroenterol Nutr. 1999;28(5):495-501. | Included for systematic reviews not completed
706 | Fonseca, A. L.,Albernaz, E. P.,Kaufmann, C. C.,Neves, I. H.,Figueiredo, V. L. Impact of breastfeeding on the intelligence quotient of eight-year-old children. J Pediatr (Rio J). 2013;89(4):346-53. | Independent variable
707 | Fonseca, M. J.,Moreira, A.,Moreira, P.,Delgado, L.,Teixeira, V.,Padrão, P. Duration of breastfeeding and the risk of childhood asthma in children living in urban areas. Journal of Investigational Allergology and Clinical Immunology. 2010;20(4):357-358. | Study design
708 | Fonseca, M. J.,Severo, M.,Barros, H.,Santos, A. C. Determinants of weight changes during the first 96 hours of life in full-term newborns. Birth. 2014;41(2):160-8. | Study design, Independent variable
709 | Fonseca, W.,Kirkwood, B. R.,Victora, C. G.,Fuchs, S. R.,Flores, J. A.,Misago, C. Risk factors for childhood pneumonia among the urban poor in Fortaleza, Brazil: a case--control study. Bull World Health Organ. 1996;74(2):199-208. | Included for systematic reviews not completed
710 | Ford, K.,Labbok, M. Breast-feeding and child health in the United States. J Biosoc Sci. 1993;25(2):187-94. | Study design
711 | Ford, R. P.,Taylor, B. J.,Mitchell, E. A.,Enright, S. A.,Stewart, A. W.,Becroft, D. M.,Scragg, R.,Hassall, I. B.,Barry, D. M.,Allen, E. M.,et al.,. Breastfeeding and the risk of sudden infant death syndrome. Int J Epidemiol. 1993;22(5):885-90. | Study design
712 | Ford-Jones, E. L.,Wang, E.,Petric, M.,Corey, P.,Moineddin, R.,Fearon, M. Hospitalization for community-acquired, rotavirus-associated diarrhea: a prospective, longitudinal, population-based study during the seasonal outbreak. The Greater Toronto Area/Peel Region PRESI Study Group. Pediatric Rotavirus Epidemiology Study for Immunization. Arch Pediatr Adolesc Med. 2000;154(6):578-85. | Study design, Health status
713 | Forman, M. R.,Graubard, B. I.,Hoffman, H. J.,Beren, R.,Harley, E. E.,Bennett, P. The Pima Infant Feeding Study: breast feeding and gastroenteritis in the first year of life. Am J Epidemiol. 1984;119(3):335-49. | Study design
714 | Forman, M. R.,Graubard, B. I.,Hoffman, H. J.,Beren, R.,Harley, E. E.,Bennett, P. The Pima infant feeding study: breastfeeding and respiratory infections during the first year of life. Int J Epidemiol. 1984;13(4):447-53. | Study design, Independent variable
715 | Forman, M. R.,Guptill, K. S.,Chang, D. N.,Sarov, B.,Berendes, H. W.,Naggan, L.,Hundt, G. L. Undernutrition among Bedouin Arab infants: the Bedouin Infant Feeding Study. Am J Clin Nutr. 1990;51(3):343-9. | Included for systematic reviews not completed
716 | Forman, M. R.,Lewando-Hundt, G.,Graubard, B. I.,Chang, D.,Sarov, B.,Naggan, L.,Berendes, H. W. Factors influencing milk insufficiency and its long-term health effects: the Bedouin Infant Feeding Study. Int J Epidemiol. 1992;21(1):53-8. | Dependent variable
717 | Forns, J.,Torrent, M.,Garcia-Esteban, R.,Caceres, A.,Pilar Gomila, M.,Martinez, D.,Morales, E.,Julvez, J.,Grimalt, J. O.,Sunyer, J. Longitudinal association between early life socio-environmental factors and attention function at the age 11 years. Environ Res. 2012;117:54-9. | Included for systematic reviews not completed
718 | Forns, J.,Vegas, O.,Julvez, J.,Garcia-Esteban, R.,Rivera, M.,Lertxundi, N.,Guxens, M.,Fano, E.,Ferrer, M.,Grellier, J.,Ibarluzea, J.,Sunyer, J. Association between child cortisol levels in saliva and neuropsychological development during the second year of life. Stress Health. 2014;30(2):142-8. | Independent variable, Dependent variable
719 | Foroushani, A. R.,Mohammad, K.,Mahmoodi, M.,Siassi, F. Effect of breastfeeding on cognitive performance in a British birth cohort. East Mediterr Health J. 2010;16(2):202-8. | Included for systematic reviews not completed
720 | Forssell, G.,Hakansson, A.,Mansson, N. O. Risk factors for respiratory tract infections in children aged 2-5 years. Scand J Prim Health Care. 2001;19(2):122-5. | Study design
721 | Forster, D. A.,Johns, H.,Amir, L. H.,McLachlan, H. L.,Moorhead, A.,Ford, R.,McEgan, K. The MILC Study—Exploring the prevalence and outcomes associated with breast milk expression: A prospective cohort study. Women & Birth. 2013;26:S7-S7 1p. | Study design
722 | Fosarelli, P. D.,DeAngelis, C.,Winkelstein, J.,Mellits, E. D. Infectious illnesses in the first two years of life. Pediatr Infect Dis. 1985;4(2):153-9. | Included for systematic reviews not completed
723 | Foulon, S.,Pingault, J. B.,Larroque, B.,Melchior, M.,Falissard, B.,Cote, S. M. Developmental predictors of inattention-hyperactivity from pregnancy to early childhood. PLoS One. 2015;10(5):e0125996. | Included for systematic reviews not completed
724 | France, G. L.,Marmer, D. J.,Steele, R. W. Breast-feeding and Salmonella infection. Am J Dis Child. 1980;134(2):147-52. | Study design
725 | Frank, A. L.,Taber, L. H.,Glezen, W. P.,Kasel, G. L.,Wells, C. R.,Paredes, A. Breast-feeding and respiratory virus infection. Pediatrics. 1982;70(2):239-45. | Independent variable
726 | Franklin PD. Exclusive Breastfeeding Duration in Relationship to Infant Risk for Overweight and Obesity at Three Years of Age: George Mason University; 2013. [thesis] | Study design
727 | Franks, A. Breastfeeding in the neonatal unit. N Z Nurs J. 1989;82(8):23-4. | Study design
728 | Fransoo, R. R.,Roos, N. P.,Martens, P. J.,Heaman, M.,Levin, B.,Chateau, D. How health status affects progress and performance in school: a population-based study. Can J Public Health. 2008;99(4):344-9. | Included for systematic reviews not completed
729 | Freeman, K.,Bonuck, K. A.,Trombley, M. Breastfeeding and infant illness in low-income, minority women: a prospective cohort study of the dose-response relationship. J Hum Lact. 2008;24(1):14-22; quiz 23-6. | Included for systematic reviews not completed
730 | Freeman, V. E.,Mulder, J.,van’t Hof, M. A.,Hoey, H. M.,Gibney, M. J. A longitudinal study of iron status in children at 12, 24 and 36 months. Public Health Nutr. 1998;1(2):93-100. | Independent variable
731 | Friel, J. K.,Andrews, W. L.,Simmons, B. S.,L’Abbe, M. R.,Mercer, C.,MacDonald, A.,McCloy, U. R. Evaluation of full-term infants fed an evaporated milk formula. Acta Paediatr. 1997;86(5):448-53. | Group size
732 | Froom, J.,Culpepper, L.,Green, L. A.,de Melker, R. A.,Grob, P.,Heeren, T.,van Balen, F. A cross-national study of acute otitis media: risk factors, severity, and treatment at initial visit. Report from the International Primary Care Network (IPCN) and the Ambulatory Sentinel Practice Network (ASPN). J Am Board Fam Pract. 2001;14(6):406-17. | Study design
733 | Froozani, M. D.,Malekafzali, H.,Bahrini, B. Growth of a group of low income infants in the first year of life. J Trop Pediatr. 1980;26(3):96-8. | Study design, Independent variable
734 | Froozani, M. D.,Permehzadeh, K.,Motlagh, A. R.,Golestan, B. Effect of breastfeeding education on the feeding pattern and health of infants in their first 4 months in the Islamic Republic of Iran. Bull World Health Organ. 1999;77(5):381-5. | Included for systematic reviews not completed
735 | Fruhwirth, M.,Heininger, U.,Ehlken, B.,Petersen, G.,Laubereau, B.,Moll-Schuler, I.,Mutz, I.,Forster, J. International variation in disease burden of rotavirus gastroenteritis in children with community- and nosocomially acquired infection. Pediatr Infect Dis J. 2001;20(8):784-91. | Health status
736 | Frye, C.,Heinrich, J. Trends and predictors of overweight and obesity in East German children. Int J Obes Relat Metab Disord. 2003;27(8):963-9. | Included for systematic reviews not completed
737 | Fuchs, S. C.,Victora, C. G. Risk and prognostic factors for diarrheal disease in Brazilian infants: a special case-control design application. Cad Saude Publica. 2002;18(3):773-82. | Included for systematic reviews not completed
738 | Fuchs, S. C.,Victora, C. G.,Martines, J. Case-control study of risk of dehydrating diarrhoea in infants in vulnerable period after full weaning. BMJ. 1996;313(7054):391-4. | Included for systematic reviews not completed
739 | Fuiano, N.,Rapa, A.,Monzani, A.,Pietrobelli, A.,Diddi, G.,Limosani, A.,Bona, G. Prevalence and risk factors for overweight and obesity in a population of Italian schoolchildren: a longitudinal study. J Endocrinol Invest. 2008;31(11):979-84. | Included for systematic reviews not completed
740 | Fujita, H.,Okada, T.,Inami, I.,Makimoto, M.,Hosono, S.,Minato, M.,Takahashi, S.,Mugishima, H.,Yamamoto, T. Low-density lipoprotein profile changes during the neonatal period. J Perinatol. 2008;28(5):335-40. | Independent variable
741 | Fujiwara, T.,Oguni, T.,Unishi, G.,Tanabe, T.,Ohbayashi, K.,Kaneko, K. Factors related to patterns of body mass index in early infancy: 18 month longitudinal study. Pediatr Int. 2014;56(3):406-10. | Independent variable
742 | Fullerton, K. E.,Ingram, L. A.,Jones, T. F.,Anderson, B. J.,McCarthy, P. V.,Hurd, S.,Shiferaw, B.,Vugia, D.,Haubert, N.,Hayes, T.,Wedel, S.,Scallan, E.,Henao, O.,Angulo, F. J. Sporadic campylobacter infection in infants: a population-based surveillance case-control study. Pediatr Infect Dis J. 2007;26(1):19-24. | Included for systematic reviews not completed
743 | Further evidence that breast is best. RCM Midwives. 2004:2-2 1p. | Study design
744 | Gabriel, C. G.,Corso, A. C.,Caldeira, G. V.,Gimeno, S. G.,Schmitz Bde, A.,de Vasconcelos Fde, A. Overweight and obesity related factors in schoolchildren in Santa Catarina State, Brazil. Arch Latinoam Nutr. 2010;60(4):332-9. | Study design
745 | Gabriele, C.,Silva, L. M.,Arends, L. R.,Raat, H.,Moll, H. A.,Hofman, A.,Jaddoe, V. W.,de Jongste, J. C. Early respiratory morbidity in a multicultural birth cohort: the Generation R Study. Eur J Epidemiol. 2012;27(6):453-62. | Dependent variable
746 | Gaffney, K. F.,Kitsantas, P.,Cheema, J. Clinical practice guidelines for feeding behaviors and weight-for-age at 12 months: a secondary analysis of the Infant Feeding Practices Study II. Worldviews Evid Based Nurs. 2012;9(4):234-42. | Independent variable
747 | Galan-Gonzalez AF,Aznar-Martin T,Cabrera-Dominguez ME,Dominguez-Reyes A. Do breastfeeding and bottle feeding influence occlusal parameters?. Breastfeed Med. 2014;9:24-8. | Study design
748 | Galán-Gónzalez, A. F.,Aznar-Martín, T.,Cabrera-Domínguez, M. E.,Domínguez-Reyes, A. Do breastfeeding and bottle feeding influence occlusal parameters?. Breastfeeding Medicine. 2014;9(1):24-28. | Study design
749 | Gale, C. R.,Marriott, L. D.,Martyn, C. N.,Limond, J.,Inskip, H. M.,Godfrey, K. M.,Law, C. M.,Cooper, C.,West, C.,Robinson, S. M. Breastfeeding, the use of docosahexaenoic acid-fortified formulas in infancy and neuropsychological function in childhood. Arch Dis Child. 2010;95(3):174-9. | Included for systematic reviews not completed
750 | Gale, C. R.,Martyn, C. N. Breastfeeding, dummy use, and adult intelligence. Lancet. 1996;347(9008):1072-5. | Included for systematic reviews not completed
751 | Gale, C. R.,Martyn, C. N.,Marriott, L. D.,Limond, J.,Crozier, S.,Inskip, H. M.,Godfrey, K. M.,Law, C. M.,Cooper, C.,Robinson, S. M. Dietary patterns in infancy and cognitive and neuropsychological function in childhood. Journal of Child Psychology and Psychiatry and Allied Disciplines. 2009;50(7):816-823. | Independent variable
752 | Gale, C.,Thomas, E. L.,Jeffries, S.,Durighel, G.,Logan, K. M.,Parkinson, J. R.,Uthaya, S.,Santhakumaran, S.,Bell, J. D.,Modi, N. Adiposity and hepatic lipid in healthy full-term, breastfed, and formula-fed human infants: a prospective short-term longitudinal cohort study. Am J Clin Nutr. 2014;99(5):1034-40. | Group size
753 | Galler, J. R.,Harrison, R. H.,Ramsey, F.,Forde, V.,Butler, S. C. Maternal depressive symptoms affect infant cognitive development in Barbados. J Child Psychol Psychiatry. 2000;41(6):747-57. | Independent variable
754 | Galler, J. R.,Ramsey, F. C.,Harrison, R. H.,Brooks, R.,Weiskopf-Bock, S. Infant feeding practices in Barbados predict later growth. J Nutr. 1998;128(8):1328-35. | Independent variable
755 | Galler, J. R.,Ramsey, F. C.,Harrison, R. H.,Taylor, J.,Cumberbatch, G.,Forde, V. Postpartum maternal moods and infant size predict performance on a national high school entrance examination. J Child Psychol Psychiatry. 2004;45(6):1064-75. | Included for systematic reviews not completed
756 | Gallico R,Hokemeyer C. SIDS project offers delactation advice. NAACOG Newsl. 1987;14:4-5. | Study design
757 | Garcia, M. V.,Azevedo, M. F.,Testa, J. R.,Luiz, C. B. The influence of the type of breastfeeding on middle ear conditions in infants. Braz J Otorhinolaryngol. 2012;78(1):8-14. | Study design
758 | Garcia-Marcos, L.,Mallol, J.,Sole, D.,Brand, P. L. International study of wheezing in infants: risk factors in affluent and non-affluent countries during the first year of life. Pediatr Allergy Immunol. 2010;21(5):878-88. | Study design
759 | Garcia-Marcos, L.,Mallol, J.,Sole, D.,Brand, P. L.,Sanchez-Bahillo, M.,Sanchez-Solis, M. Latitude modifies the effect size of factors related to recurrent wheeze in the first year of life. Respir Med. 2013;107(5):665-72. | Study design, Dependent variable
760 | Garden, F. L.,Marks, G. B.,Simpson, J. M.,Webb, K. L. Body mass index (BMI) trajectories from birth to 11.5 years: relation to early life food intake. Nutrients. 2012;4(10):1382-98. | Included for systematic reviews not completed
761 | Garmendia, M. L.,Corvalan, C.,Araya, M.,Casanello, P.,Kusanovic, J. P.,Uauy, R. Effectiveness of a normative nutrition intervention (diet, physical activity and breastfeeding) on maternal nutrition and offspring growth: the Chilean maternal and infant nutrition cohort study (CHiMINCs). BMC Pregnancy Childbirth. 2015;15:175. | Study design, Independent variable
762 | Garry, P. J.,Owen, G. M.,Hooper, E. M.,Gilbert, B. A. Iron absorption from human milk and formula with and without iron supplementation. Pediatr Res. 1981;15(5):822-8. | Included for systematic reviews not completed
763 | Garza, C. The INTERGROWTH-21st project and the multicenter growth reference study: enhanced opportunities for monitoring growth from early pregnancy to 5 years of age. Breastfeed Med. 2014;9(7):341-4. | Study design
764 | Garza, C.,Borghi, E.,Onyango, A. W.,de Onis, M. Parental height and child growth from birth to 2 years in the WHO Multicentre Growth Reference Study. Matern Child Nutr. 2013;9 Suppl 2:58-68. | Included for systematic reviews not completed
765 | Gathwala, G.,Narang, A. Breast is best. Indian J Pediatr. 1995;62(6):687-90. | Study design
766 | Geller-Bernstein, G.,Kenett, R.,Weisglass, L.,Tsur, S.,Lahav, M.,Levin, S. Atopic babies with wheezy bronchitis. Follow-up study relating prognosis to sequential IgE values, type of early infant feeding, exposure to parental smoking and incidence of lower respiratory tract infections. Allergy. 1987;42(2):85-91. | Dependent variable
767 | Gerrard, J. W. Allergies in breastfed babies to foods ingested by the mother (review). Clin Rev Allergy. 1984;2(2):143-9. | Study design
768 | Gerrard, J. W.,Shenassa, M. Food allergy: two common types as seen in breast and formula fed babies. Ann Allergy. 1983;50(6):375-9. | Study design
769 | Gessner, B. D.,Ussery, X. T.,Parkinson, A. J.,Breiman, R. F. Risk factors for invasive disease caused by Streptococcus pneumoniae among Alaska native children younger than two years of age. Pediatr Infect Dis J. 1995;14(2):123-8. | Group size
770 | Ghosh, S.,Sengupta, P. G.,Mondal, S. K.,Banu, M. K.,Gupta, D. N.,Sircar, B. K. Risk behavioural practices of rural mothers as determinants of childhood diarrhoea. J Commun Dis. 1997;29(1):7-14. | Country
771 | Ghys, A.,Bakker, E.,Hornstra, G.,van den Hout, M. Red blood cell and plasma phospholipid arachidonic and docosahexaenoic acid levels at birth and cognitive development at 4 years of age. Early Hum Dev. 2002;69(1-2):83-90. | Study design
772 | Gianino, P.,Mastretta, E.,Longo, P.,Laccisaglia, A.,Sartore, M.,Russo, R.,Mazzaccara, A. Incidence of nosocomial rotavirus infections, symptomatic and asymptomatic, in breast-fed and non-breast-fed infants. Journal of Hospital Infection. 2002;50(1):13-17. | Study design
773 | Gianni, M. L.,Roggero, P.,Baudry, C.,Ligneul, A.,Morniroli, D.,Garbarino, F.,le Ruyet, P.,Mosca, F. The influence of a formula supplemented with dairy lipids and plant oils on the erythrocyte membrane omega-3 fatty acid profile in healthy full-term infants: a double-blind randomized controlled trial. BMC Pediatr. 2012;12:164. | Independent variable
774 | Gianni, M. L.,Roggero, P.,Morlacchi, L.,Garavaglia, E.,Piemontese, P.,Mosca, F. Formula-fed infants have significantly higher fat-free mass content in their bodies than breastfed babies. Acta Paediatr. 2014;103(7):e277-81. | Included for systematic reviews not completed
775 | Gibbs, B. G.,Forste, R. Breastfeeding, parenting, and early cognitive development. J Pediatr. 2014;164(3):487-93. | Included for systematic reviews not completed
776 | Gibbs, B. G.,Forste, R. Socioeconomic status, infant feeding practices and early childhood obesity. Pediatr Obes. 2014;9(2):135-46. | Included for systematic reviews not completed
777 | Gibson-Davis, C. M.,Brooks-Gunn, J. Breastfeeding and verbal ability of 3-year-olds in a multicity sample. Pediatrics. 2006;118(5):e1444-51. | Included for systematic reviews not completed
778 | Gigante, D. P.,Horta, B. L.,Lima, R. C.,Barros, F. C.,Victora, C. G. Early life factors are determinants of female height at age 19 years in a population-based birth cohort (Pelotas, Brazil). J Nutr. 2006;136(2):473-8. | Included for systematic reviews not completed
779 | Gilbert, R. E.,Wigfield, R. E.,Fleming, P. J.,Berry, P. J.,Rudd, P. T. Bottle feeding and the sudden infant death syndrome. BMJ. 1995;310(6972):88-90. | Included for systematic reviews not completed
780 | Gilbert, R. The changing epidemiology of SIDS. Arch Dis Child. 1994;70(5):445-9. | Study design
781 | Gillman, M. W.,Rifas-Shiman, S. L.,Berkey, C. S.,Frazier, A. L.,Rockett, H. R.,Camargo, C. A., Jr.,Field, A. E.,Colditz, G. A. Breast-feeding and overweight in adolescence: within-family analysis [corrected]. Epidemiology. 2006;17(1):112-4. | Included for systematic reviews not completed
782 | Gillman, M. W.,Rifas-Shiman, S. L.,Camargo, C. A., Jr.,Berkey, C. S.,Frazier, A. L.,Rockett, H. R.,Field, A. E.,Colditz, G. A. Risk of overweight among adolescents who were breastfed as infants. JAMA. 2001;285(19):2461-7. | Study design
783 | Gillman, M. W.,Rifas-Shiman, S. L.,Kleinman, K.,Oken, E.,Rich-Edwards, J. W.,Taveras, E. M. Developmental origins of childhood overweight: potential public health impact. Obesity (Silver Spring). 2008;16(7):1651-6. | Included for systematic reviews not completed
784 | Gimenez-Sanchez, F.,Delgado-Rubio, A.,Martinon-Torres, F.,Bernaola-Iturbe, E. Multicenter prospective study analysing the role of rotavirus on acute gastroenteritis in Spain. Acta Paediatr. 2010;99(5):738-42. | Study design, Health status
785 | Giovannini, M.,Agostoni, C.,Fiocchi, A.,Bellu, R.,Trojan, S.,Riva, E. Antigen-reduced infant formulas versus human milk: growth and metabolic parameters in the first 6 months of life. J Am Coll Nutr. 1994;13(4):357-63. | Group size
786 | Giovannini, M.,Verduci, E.,Zuccotti, G.,Biasucci, G.,Podesta, A.,Rottoli, A.,Gregori, D.,Ballali, S.,Banderali, G.,Riva, E.,Ghisleni, D.,Pogliani, L.,Cicero, C.,Tonella, M.,Frugnoli, I. Safety of a formula supplemented with galacto-oligosaccharides in term infants. International journal of probiotics & prebiotics. 2013;8(2-3):67-74. | Included for systematic reviews not completed
787 | Giovannini, M.,Verduci, E.,Zuccotti, G.,Biasucci, G.,Podesta, A.,Rottoli, A.,Gregori, D.,Ballali, S.,Soldi, S.,Banderali, G.,Ghisleni, D.,Riva, E. Prebiotic effect of a formula supplemented with galacto-oligosaccharides in term infants: A randomized multicenter trial. Annals of nutrition & metabolism. 2013;63:1667. | Study design
788 | Gishti, O.,Jaddoe, V. W.,Duijts, L.,Franco, O. H.,Hofman, A.,Ikram, M. K.,Gaillard, R. Influence of breastfeeding on retinal vessel calibers in school-age children. The Generation R Study. Eur J Clin Nutr. 2015. | Dependent variable
789 | Giugliano, L. G.,Meyer, C. J.,Arantes, L. C.,Ribeiro, S. T.,Giugliano, R. Mannose-resistant haemagglutination (MRHA) and haemolysin (Hly) production of strains of Escherichia coli isolated from children with diarrhoea: effect of breastfeeding. J Trop Pediatr. 1993;39(3):183-7. | Study design, Health status
790 | Giwercman, C.,Halkjaer, L. B.,Jensen, S. M.,Bonnelykke, K.,Lauritzen, L.,Bisgaard, H. Increased risk of eczema but reduced risk of early wheezy disorder from exclusive breast-feeding in high-risk infants. J Allergy Clin Immunol. 2010;125(4):866-71. | Independent variable
791 | Glatthaar, C.,Whittall, D. E.,Welborn, T. A.,Gibson, M. J.,Brooks, B. H.,Ryan, M. M.,Byrne, G. C. Diabetes in Western Australian children: descriptive epidemiology. Med J Aust. 1988;148(3):117-23. | Independent variable
792 | Gliddon, M. L.,Sutton, G. Prediction of 8-month MEE from neonatal risk factors and test results in SCBU and full-term babies. British Journal of Audiology. 2001;35(1):77-85. | Non-human, Health status
793 | Glueck, C. J.,Salehi, M.,Sieve, L.,Wang, P. Growth, motor, and social development in breast- and formula-fed infants of metformin-treated women with polycystic ovary syndrome. J Pediatr. 2006;148(5):628-632. | Included for systematic reviews not completed
794 | Gokcay, G.,Turan, J. M.,Partalci, A.,Neyzi, O. Growth of infants during the first year of life according to feeding regimen in the first 4 months. J Trop Pediatr. 2003;49(1):6-12. | Included for systematic reviews not completed
795 | Goldfield, G. S.,Paluch, R.,Keniray, K.,Hadjiyannakis, S.,Lumb, A. B.,Adamo, K. Effects of breastfeeding on weight changes in family-based pediatric obesity treatment. J Dev Behav Pediatr. 2006;27(2):93-7. | Health status
796 | Golding, J.,Rogers, I. S.,Emmett, P. M. Breast feeding: benefits and hazards. Methodology and summary of results. Early Hum Dev. 1997;49 Suppl:S1-6. | Study design
797 | Gomez-Sanchiz, M.,Canete, R.,Rodero, I.,Baeza, J. E.,Avila, O. Influence of breast-feeding on mental and psychomotor development. Clin Pediatr (Phila). 2003;42(1):35-42. | Included for systematic reviews not completed
798 | Gomez-Sanchiz, M.,Canete, R.,Rodero, I.,Baeza, J. E.,Gonzalez, J. A. Influence of breast-feeding and parental intelligence on cognitive development in the 24-month-old child. Clin Pediatr (Phila). 2004;43(8):753-61. | Included for systematic reviews not completed
799 | Gong, Y. H.,Ji, C. Y.,Zheng, X. X.,Shan, J. P.,Hou, R. Correlation of 4-month infant feeding modes with their growth and iron status in Beijing. Chin Med J (Engl). 2008;121(5):392-8. | Independent variable
800 | Gonzalez-Casanova, I.,Stein, A.,Hao, W.,Feregrino, R.,Romieu, I.,Barraza-Villarreal, A.,Rivera, J.,Martorell, R.,Ramakrishnan, U. Height and BMI at five years of age following prenatal supplementation with docosahexaenoic acid in Mexico. FASEB journal. 2014;28(1 suppl. 1). | Peer review
801 | Gopalan, S.,Puri, R. K. Breast feeding and infant growth. Indian Pediatr. 1992;29(8):1079-86. | Study design
802 | Gopinath, V. K.,Muda, W. A. Assessment of growth and feeding practices in children with cleft lip and palate. Southeast Asian J Trop Med Public Health. 2005;36(1):254-8. | Independent variable, Dependent variable
803 | Gordon, M. Why breastfeeding is best for babies. Health Visit. 1995;68(5):203-4. | Study design
804 | Gordon, R. R.,Noble, D. A.,Ward, A. M.,Allen, R. Immunoglobulin E and the eczema-asthma syndrome in early childhood. Lancet. 1982;1(8263):72-4. | Dependent variable
805 | Gore, C.,Custovic, A.,Tannock, G. W.,Munro, K.,Kerry, G.,Johnson, K.,Peterson, C.,Morris, J.,Chaloner, C.,Murray, C. S.,Woodcock, A. Treatment and secondary prevention effects of the probiotics Lactobacillus paracasei or Bifidobacterium lactis on early infant eczema: randomized controlled trial with follow-up until age 3 years. Clin Exp Allergy. 2012;42(1):112-22. | Health status
806 | Gore, C.,Munro, K.,Lay, C.,Bibiloni, R.,Morris, J.,Woodcock, A.,Custovic, A.,Tannock, G. W. Bifidobacterium pseudocatenulatum is associated with atopic eczema: a nested case-control study investigating the fecal microbiota of infants. J Allergy Clin Immunol. 2008;121(1):135-40. | Group size
807 | Gore, N.,Emerson, E.,Brady, S. Rates of breastfeeding and exposure to socio-economic adversity amongst children with intellectual disability. Res Dev Disabil. 2015;39:12-9. | Included for systematic reviews not completed
808 | Gormally, S. M.,Matthews, T. G. Contemporary risk factors for sudden infant death in an Irish population--a case control study. Ir J Med Sci. 1992;161(5):131-4. | Included for systematic reviews not completed
809 | Gracey, M. Maternal health, breast-feeding and infant nutrition in Australian aborigines. Acta Paediatr Jpn. 1989;31(4):377-80. | Study design
810 | Grainger, M. Breastfeeding can reduce infant infections and health care costs. Ala Nurse. 2006;33(3):23. | Study design
811 | Graves, J.,Grandhe, S.,Weinfurtner, K.,Krupp, L.,Belman, A.,Chitnis, T.,Ness, J.,Weinstock-Guttman, B.,Gorman, M.,Patterson, M.,Rodriguez, M.,Lotze, T.,Aaen, G.,Mowry, E. M.,Rose, J. W.,Simmons, T.,Casper, T. C.,James, J.,Waubant, E. Protective environmental factors for neuromyelitis optica. Neurology. 2014;83(21):1923-9. | Dependent variable
812 | Greasley, V. Breast feeding. Nursing (Lond). 1986;3(2):63-70. | Study design
813 | Green, Ken. UC Denver Study: Breastfeeding Can Prevent Diabetes-Related Childhood Obesity. Inside Childbirth Education. 2012:10-10 1p. | Study design
814 | Greene, L. C.,Lucas, A.,Livingstone, M. B.,Harland, P. S.,Baker, B. A. Relationship between early diet and subsequent cognitive performance during adolescence. Biochem Soc Trans. 1995;23(2):376S. | Included for systematic reviews not completed
815 | Greer MH,Tendan SL. Early childhood dental caries in Hawai’i. Hawaii Dent J. 1998;29:10, 14. | Study design
816 | Grguric, J.,Wen, R. A.,Kylberg, E.,Ashmore, S.,Macenroe, T. International perspectives on the Baby-Friendly Initiative. J Hum Lact. 2012;28(3):281-4. | Study design
817 | Grice, A. C.,McGlashan, N. D. Obstetric factors in 171 sudden infant deaths in Tasmania, 1970--1976. Med J Aust. 1981;1(1):26-31. | Included for systematic reviews not completed
818 | Griffiths, L. J.,Hawkins, S. S.,Cole, T. J.,Dezateux, C. Risk factors for rapid weight gain in preschool children: Findings from a UK-wide prospective study. International Journal of Obesity. 2010;34(4):624-632. | Included for systematic reviews not completed
819 | Griffiths, L. J.,Smeeth, L.,Hawkins, S. S.,Cole, T. J.,Dezateux, C. Effects of infant feeding practice on weight gain from birth to 3 years. Arch Dis Child. 2009;94(8):577-82. | Included for systematic reviews not completed
820 | Grjibovski, A. M.,Bygren, L. O.,Yngve, A.,Sjostrom, M. Social variations in infant growth performance in Severodvinsk, Northwest Russia: community-based cohort study. Croat Med J. 2004;45(6):757-63. | Included for systematic reviews not completed
821 | Groen-Blokhuis, M. M.,Franic, S.,van Beijsterveldt, C. E.,de Geus, E.,Bartels, M.,Davies, G. E.,Ehli, E. A.,Xiao, X.,Scheet, P. A.,Althoff, R.,Hudziak, J. J.,Middeldorp, C. M.,Boomsma, D. I. A prospective study of the effects of breastfeeding and FADS2 polymorphisms on cognition and hyperactivity/attention problems. Am J Med Genet B Neuropsychiatr Genet. 2013;162B(5):457-65. | Included for systematic reviews not completed
822 | Groenwold, R. H.,Tilling, K.,Moons, K. G.,Hoes, A. W.,van der Ent, C. K.,Kramer, M. S.,Martin, R. M.,Sterne, J. A. Breast-feeding and health consequences in early childhood: is there an impact of time-dependent confounding?. Ann Nutr Metab. 2014;65(2-3):139-48. | Independent variable
823 | Grossman, X.,Chaudhuri, J. H.,Feldman-Winter, L.,Merewood, A. Neonatal weight loss at a US Baby-Friendly Hospital. J Acad Nutr Diet. 2012;112(3):410-3. | Group size
824 | Grube, M. M.,von der Lippe, E.,Schlaud, M.,Brettschneider, A. K. Does breastfeeding help to reduce the risk of childhood overweight and obesity? A propensity score analysis of data from the KiGGS study. PLoS One. 2015;10(3):e0122534. | Study design
825 | Gruber, C.,van Stuijvenberg, M.,Mosca, F.,Moro, G.,Chirico, G.,Braegger, C. P.,Riedler, J.,Boehm, G.,Wahn, U. Reduced occurrence of early atopic dermatitis because of immunoactive prebiotics among low-atopy-risk infants. J Allergy Clin Immunol. 2010;126(4):791-7. | Independent variable
826 | Gruber, M.,Marshall, J. R.,Zielezny, M.,Lance, P. A case-control study to examine the influence of maternal perinatal behaviors on the incidence of Crohn’s disease. Gastroenterol Nurs. 1996;19(2):53-9. | Study design
827 | Grummer-Strawn, L. M.,Li, R.,Perrine, C. G.,Scanlon, K. S.,Fein, S. B. Infant feeding and long-term outcomes: results from the year 6 follow-up of children in the Infant Feeding Practices Study II. Pediatrics. 2014;134 Suppl 1:S1-3. | Study design
828 | Grummer-Strawn, L. M.,Mei, Z. Does breastfeeding protect against pediatric overweight? Analysis of longitudinal data from the Centers for Disease Control and Prevention Pediatric Nutrition Surveillance System. Pediatrics. 2004;113(2):e81-6. | Included for systematic reviews not completed
829 | Gruskay, F. L. Comparison of breast, cow, and soy feedings in the prevention of onset of allergic disease: a 15-year prospective study. Clin Pediatr (Phila). 1982;21(8):486-91. | Independent variable
830 | Gruszfeld, D.,Weber, M.,Nowakowska-Rysz, M.,Janas, R.,Kozlik-Feldmann, R.,Xhonneux, A.,Carlier, C.,Riva, E.,Verduci, E.,Closa-Monasterolo, R.,Escribano, J.,Dobrzanska, A.,Koletzko, B. Protein intake in infancy and carotid intima media thickness at 5 years--a secondary analysis from a randomized trial. Ann Nutr Metab. 2015;66(1):51-9. | Independent variable
831 | Gubbels, J. S.,Thijs, C.,Stafleu, A.,van Buuren, S.,Kremers, S. P. Association of breast-feeding and feeding on demand with child weight status up to 4 years. Int J Pediatr Obes. 2011;6(2-2):e515-22. | Included for systematic reviews not completed
832 | Gudino, S.,Rojas, N.,Castro, C.,Rodriguez, M.,Vega, M.,Lopez, L. M. Colonization of mutans streptococci in Costa Rican children from a high-risk population. J Dent Child (Chic). 2007;74(1):36-40. | Study design
833 | Guedes, H. T.,Souza, L. S. Exposure to maternal smoking in the first year of life interferes in breast-feeding protective effect against the onset of respiratory allergy from birth to 5 yr. Pediatr Allergy Immunol. 2009;20(1):30-4. | Independent variable
834 | Guerrero, M. L.,Moreno-Espinosa, S.,Tuz-Dzib, F.,Solis-Albino, J.,Ortega-Gallegos, H.,Ruiz-Palacios, G. M. Breastfeeding and natural colonization with Lactobacillus spp as protection against rotavirus-associated diarrhea. Adv Exp Med Biol. 2004;554:451-5. | Peer review
835 | Guibas, G. V.,Xepapadaki, P.,Moschonis, G.,Douladiris, N.,Filippou, A.,Tsirigoti, L.,Manios, Y.,Papadopoulos, N. G. Breastfeeding and wheeze prevalence in pre-schoolers and pre-adolescents: the Genesis and Healthy Growth studies. Pediatr Allergy Immunol. 2013;24(8):772-81. | Study design
836 | Guldan, G. S.,Fan, H. C.,Ma, X.,Ni, Z. Z.,Xiang, X.,Tang, M. Z. Culturally appropriate nutrition education improves infant feeding and growth in rural Sichuan, China. J Nutr. 2000;130(5):1204-11. | Study design, Dependent variable
837 | Gulick EE. The effects of breast-feeding on toddler health. Pediatr Nurs. 1986;12:51-4. | Dependent variable
838 | Gulick, E. E. Infant health and breast-feeding. Pediatr Nurs. 1983;9(5):359-62, 389. | Study design
839 | Gunderson, E. P. Breastfeeding after gestational diabetes pregnancy: subsequent obesity and type 2 diabetes in women and their offspring. Diabetes Care. 2007;30 Suppl 2:S161-8. | Study design
840 | Gunderson, E. P.,Hurston, S. R.,Dewey, K. G.,Faith, M. S.,Charvat-Aguilar, N.,Khoury, V. C.,Nguyen, V. T.,Quesenberry, C. P., Jr. The study of women, infant feeding and type 2 diabetes after GDM pregnancy and growth of their offspring (SWIFT Offspring study): prospective design, methodology and baseline characteristics. BMC Pregnancy Childbirth. 2015;15:150. | Study design
841 | Gungor, D. E.,Paul, I. M.,Birch, L. L.,Bartok, C. J. Risky vs rapid growth in infancy: refining pediatric screening for childhood overweight. Arch Pediatr Adolesc Med. 2010;164(12):1091-7. | Included for systematic reviews not completed
842 | Gunnarsdottir, I.,Aspelund, T.,Birgisdottir, B. E.,Benediktsson, R.,Gudnason, V.,Thorsdottir, I. Infant feeding patterns and midlife erythrocyte sedimentation rate. Acta Paediatr. 2007;96(6):852-6. | Independent variable
843 | Gunnarsdottir, I.,Schack-Nielsen, L.,Michaelsen, K. F.,Sorensen, T. I.,Thorsdottir, I. Infant weight gain, duration of exclusive breast-feeding and childhood BMI - two similar follow-up cohorts. Public Health Nutr. 2010;13(2):201-7. | Included for systematic reviews not completed
844 | Gunther, A. L.,Walz, H.,Kroke, A.,Wudy, S. A.,Riedel, C.,von Kries, R.,Joslowski, G.,Remer, T.,Cheng, G.,Buyken, A. E. Breastfeeding and its prospective association with components of the GH-IGF-Axis, insulin resistance and body adiposity measures in young adulthood--insights from linear and quantile regression analysis. PLoS One. 2013;8(11):e79436. | Independent variable
845 | Guo, A. Y.,Stevens, B. W.,Wilson, R. G.,Russell, C. N.,Cohen, M. A.,Sturgeon, H. C.,Thornton, A.,Giallourakis, C.,Khalili, H.,Nguyen, D. D.,Sauk, J.,Yajnik, V.,Xavier, R. J.,Ananthakrishnan, A. N. Early life environment and natural history of inflammatory bowel diseases. BMC Gastroenterol. 2014;14:216. | Study design, Dependent variable
846 | Gurkan, F.,Davutog Lu, M.,Bilici, M.,Sincar, N.,Haspolat, K. Pulmonary functions in atopic and nonatopic asthmatic children. Allergol Immunopathol (Madr). 2002;30(2):70-3. | Study design, Health status
847 | Gurkan, F.,Davutoglu, M.,Bilici, M.,Dagli, A.,Haspolat, K. Asthmatic children and risk factors at a province in the southeast of Turkey. Allergol Immunopathol (Madr). 2002;30(1):25-9. | Study design
848 | Gurnida, D. A.,Rowan, A. M.,Idjradinata, P.,Muchtadi, D.,Sekarwana, N. Association of complex lipids containing gangliosides with cognitive development of 6-month-old infants. Early Hum Dev. 2012;88(8):595-601. | Country
849 | Gurwith, M.,Wenman, W.,Gurwith, D.,Brunton, J.,Feltham, S.,Greenberg, H. Diarrhea among infants and young children in Canada: a longitudinal study in three northern communities. J Infect Dis. 1983;147(4):685-92. | Independent variable
850 | Gurwith, M.,Wenman, W.,Hinde, D.,Feltham, S.,Greenberg, H. A prospective study of rotavirus infection in infants and young children. J Infect Dis. 1981;144(3):218-24. | Group size
851 | Gustafsson, D.,Lowhagen, T.,Andersson, K. Risk of developing atopic disease after early feeding with cows’ milk based formula. Arch Dis Child. 1992;67(8):1008-10. | Independent variable
852 | Gustafsson, P. A.,Duchen, K.,Birberg, U.,Karlsson, T. Breastfeeding, very long polyunsaturated fatty acids (PUFA) and IQ at 6 1/2 years of age. Acta Paediatr. 2004;93(10):1280-7. | Included for systematic reviews not completed
853 | Guxens, M.,Aguilera, I.,Ballester, F.,Estarlich, M.,Fernandez-Somoano, A.,Lertxundi, A.,Lertxundi, N.,Mendez, M. A.,Tardon, A.,Vrijheid, M.,Sunyer, J. Prenatal exposure to residential air pollution and infant mental development: modulation by antioxidants and detoxification factors. Environ Health Perspect. 2012;120(1):144-9. | Included for systematic reviews not completed
854 | Guxens, M.,Mendez, M. A.,Molto-Puigmarti, C.,Julvez, J.,Garcia-Esteban, R.,Forns, J.,Ferrer, M.,Vrijheid, M.,Lopez-Sabater, M. C.,Sunyer, J. Breastfeeding, long-chain polyunsaturated fatty acids in colostrum, and infant mental development. Pediatrics. 2011;128(4):e880-9. | Included for systematic reviews not completed
855 | Habibzadeh, H.,Jafarizadeh, H.,Didarloo, A. Determinants of failure to thrive (FTT) among infants aged 6-24 months: a case-control study. J Prev Med Hyg. 2015;56(4):E180-6. | Included for systematic reviews not completed
856 | Habicht, J. P.,DaVanzo, J.,Butz, W. P. Does breastfeeding really save lives, or are apparent benefits due to biases?. Am J Epidemiol. 1986;123(2):279-90. | Study design
857 | Habicht, J. P.,DaVanzo, J.,Butz, W. P. Mother’s milk and sewage: their interactive effects on infant mortality. Pediatrics. 1988;81(3):456-61. | Study design
858 | Hackney, A. R. Breast feeding. Am J Nurs. 1990;90(12):70. | Study design
859 | Haddad, M. B.,Porucznik, C. A.,Joyce, K. E.,De, A. K.,Pavia, A. T.,Rolfs, R. T.,Byington, C. L. Risk factors for pediatric invasive pneumococcal disease in the Intermountain West, 1996-2002. Ann Epidemiol. 2008;18(2):139-46. | Independent variable
860 | Haider, S. J.,Chang, L. V.,Bolton, T. A.,Gold, J. G.,Olson, B. H. An evaluation of the effects of a breastfeeding support program on health outcomes. Health Serv Res. 2014;49(6):2017-34. | Independent variable, Dependent variable
861 | Haines, M. R.,Kintner, H. J. “Can breast feeding help you in later life? Evidence from German military heights in the early 20th century”. Econ Hum Biol. 2008;6(3):420-30. | Study design, Independent variable
862 | Hakansson, A.,Carlsson, B. Maternal cigarette smoking, breast-feeding, and respiratory tract infections in infancy. A population-based cohort study. Scand J Prim Health Care. 1992;10(1):60-5. | Study design, Dependent variable
863 | Halchak, B. The Oxford lactation study. J Nurse Midwifery. 1982;27(5):34-6. | Independent variable, Dependent variable
864 | Halken, S. What causes allergy and asthma? The role of dietary factors. Pediatr Pulmonol Suppl. 2004;26:223-4. | Study design
865 | Halken, S.,Hansen, K. S.,Jacobsen, H. P.,Estmann, A.,Faelling, A. E.,Hansen, L. G.,Kier, S. R.,Lassen, K.,Lintrup, M.,Mortensen, S.,Ibsen, K. K.,Osterballe, O.,Host, A. Comparison of a partially hydrolyzed infant formula with two extensively hydrolyzed formulas for allergy prevention: a prospective, randomized study. Pediatr Allergy Immunol. 2000;11(3):149-61. | Independent variable
866 | Halken, S.,Host, A.,Hansen, L. G.,Osterballe, O. Effect of an allergy prevention programme on incidence of atopic symptoms in infancy. A prospective study of 159 “high-risk” infants. Allergy. 1992;47(5):545-53. | Study design, Independent variable
867 | Halken, S.,Host, A.,Hansen, L. G.,Osterballe, O. Preventive effect of feeding high-risk infants a casein hydrolysate formula or an ultrafiltrated whey hydrolysate formula. A prospective, randomized, comparative clinical study. Pediatr Allergy Immunol. 1993;4(4):173-81. | Group size
868 | Halken, S.,Host, A.,Husby, S.,Hansen, L. G.,Osterballe, O.,Nyboe, J. Recurrent wheezing in relation to environmental risk factors in infancy. A prospective study of 276 infants. Allergy. 1991;46(7):507-14. | Dependent variable
869 | Hallonsten, A. L.,Wendt, L. K.,Mejare, I.,Birkhed, D.,Hakansson, C.,Lindvall, A. M.,Edwardsson, S.,Koch, G. Dental caries and prolonged breast-feeding in 18-month-old Swedish children. Int J Paediatr Dent. 1995;5(3):149-55. | Study design
870 | Hambraeus, L. The significance of mother’s milk and breast-feeding for development and later life. Bibl Nutr Dieta. 1982(31):1-16. | Study design
871 | Hamburger, R. N.,Heller, S.,Mellon, M. H.,O’Connor, R. D.,Zeiger, R. S. Current status of the clinical and immunologic consequences of a prototype allergic disease prevention program. Ann Allergy. 1983;51(2 Pt 2):281-90. | Study design, Independent variable
872 | Hamilton, J. J.,Synnes, A.,Innis, S. M. Plasma cholesterol and lathosterol levels in term infants in the early neonatal period. Pediatr Res. 1992;31(4 Pt 1):396-400. | Group size
873 | Hamilton, J. R. Viral diarrhea. Pediatr Ann. 1985;14(1):25-8. | Study design
874 | Han, D. H.,Ahn, J. C.,Mun, S. J.,Park, S. K.,Oh, S. Y.,Rhee, C. S. Novel risk factors for allergic rhinitis in Korean elementary school children: ARCO-kids phase II in a community. Allergy, Asthma and Immunology Research. 2015;7(3):234-240. | Study design
875 | Han, D. Y.,Fraser, A. G.,Dryland, P.,Ferguson, L. R. Environmental factors in the development of chronic inflammation: a case-control study on risk factors for Crohn’s disease within New Zealand. Mutat Res. 2010;690(1-2):116-22. | Study design
876 | Han, Y. S.,Park, H. Y.,Ahn, K. M.,Lee, J. S.,Choi, H. M.,Lee, S. I. Short-term effect of partially hydrolyzed formula on the prevention of development of atopic dermatitis in infants at high risk. J Korean Med Sci. 2003;18(4):547-51. | Group size
877 | Han, Y.,Chung, S. J.,Kim, J.,Ahn, K.,Lee, S. I. High sensitization rate to food allergens in breastfed infants with atopic dermatitis. Ann Allergy Asthma Immunol. 2009;103(4):332-6. | Study design, Dependent variable
878 | Hancox, R. J.,Stewart, A. W.,Braithwaite, I.,Beasley, R.,Murphy, R.,Mitchell, E. A. Association between breastfeeding and body mass index at age 6-7 years in an international survey. Pediatr Obes. 2015;10(4):283-7. | Study design
879 | Hanicar, B.,Mandic, Z.,Pavic, R. Exclusive breastfeeding and growth in Croatian infants--comparison to the WHO child growth standards and to the NCHS growth references. Coll Antropol. 2009;33(3):735-41. | Included for systematic reviews not completed
880 | Hanning, R. M.,Paes, B.,Atkinson, S. A. Protein metabolism and growth of term infants in response to a reduced-protein, 40:60 whey: casein formula with added tryptophan. Am J Clin Nutr. 1992;56(6):1004-11. | Included for systematic reviews not completed
881 | Hansen, K. The Power of Nutrition and the Power of Breastfeeding. Breastfeed Med. 2015;10(8):385-8. | Study design
882 | Hanson, L. A.,Ashraf, R.,Zaman, S.,Karlberg, J.,Lindblad, B. S.,Jalil, F. Breast feeding is a natural contraceptive and prevents disease and death in infants, linking infant mortality and birth rates. Acta Paediatr. 1994;83(1):3-6. | Study design
883 | Hanson, L. A.,Jalil, F.,Ashraf, R.,Bernini, S.,Carlsson, B.,Cruz, J. R.,Gonzalez, T.,Hahn-Zoric, M.,Mellander, L.,Minoli, Y.,et al.,. Characteristics of human milk antibodies and their effect in relation to the epidemiology of breastfeeding and infections in a developing country. Adv Exp Med Biol. 1991;310:1-15. | Country
884 | Happ B. Infants receive nutrition from human breast milk. NAACOG Newsl. 1986;13:1, 12-3. | Study design
885 | Haq, M. E.,Begum, K.,Muttalib, M. A.,Shahidullah, M. Prevalence of caries in urban children and its relation to feeding pattern. Bangladesh Med Res Counc Bull. 1985;11(2):55-63. | Country
886 | Hardell, L.,Dreifaldt, A. C. Breast-feeding duration and the risk of malignant diseases in childhood in Sweden. Eur J Clin Nutr. 2001;55(3):179-85. | Independent variable
887 | Hardy, E. E.,Vichi, A. M.,Sarmento, R. C.,Moreira, L. E.,Bosqueiro, C. M. Breastfeeding promotion: effect of an educational program in Brazil. Stud Fam Plann. 1982;13(3):79-86. | Dependent variable
888 | Harkin, T. Wellness and disease prevention begins at birth: the critically important role of breastfeeding. Breastfeed Med. 2011;6:245-6. | Study design
889 | Harland, B. F.,Smith, S. A.,Ellis, R.,O’Brien, R.,Morris, E. R. Comparison of the nutrient intakes of blacks, Siouan Indians, and whites in Columbus County, North Carolina. Journal of the American Dietetic Association. 1992;92(3):348-350. | Study design, Dependent variable
890 | Harris, M. C.,Kolski, G. B.,Campbell, D. E.,Deuber, C.,Marcus, M.,Douglas, S. D. Ontogeny of the antibody response to cow milk proteins. Ann Allergy. 1989;63(5):439-43. | Group size
891 | Harrison, G. G.,Graver, E. J.,Vargas, M.,Churella, H. R.,Paule, C. L. Growth and adiposity of term infants fed whey-predominant or casein-predominant formulas or human milk. J Pediatr Gastroenterol Nutr. 1987;6(5):739-47. | Group size
892 | Harrison, R.,Wong, T.,Ewan, C.,Contreras, B.,Phung, Y. Feeding practices and dental caries in an urban Canadian population of Vietnamese preschool children. ASDC J Dent Child. 1997;64(2):112-7. | Study design
893 | Harsten, G.,Prellner, K.,Heldrup, J.,Kalm, O.,Kornfalt, R. Recurrent acute otitis media. A prospective study of children during the first three years of life. Acta Otolaryngol. 1989;107(1-2):111-9. | Group size
894 | Hart, S.,Boylan, L. M.,Carroll, S.,Musick, Y. A.,Lampe, R. M. Brief report: breast-fed one-week-olds demonstrate superior neurobehavioral organization. J Pediatr Psychol. 2003;28(8):529-34. | Included for systematic reviews not completed
895 | Hartley, A. L.,Birch, J. M.,McKinney, P. A.,Blair, V.,Teare, M. D.,Carrette, J.,Mann, J. R.,Stiller, C. A.,Draper, G. J.,Johnston, H. E.,et al.,. The Inter-Regional Epidemiological Study of Childhood Cancer (IRESCC): past medical history in children with cancer. J Epidemiol Community Health. 1988;42(3):235-42. | Dependent variable
896 | Harvey, N. C.,Robinson, S. M.,Crozier, S. R.,Marriott, L. D.,Gale, C. R.,Cole, Z. A.,Inskip, H. M.,Godfrey, K. M.,Cooper, C. Breast-feeding and adherence to infant feeding guidelines do not influence bone mass at age 4 years. Br J Nutr. 2009;102(6):915-20. | Included for systematic reviews not completed
897 | Haschke, F.,van’t Hof, M. A. Euro-Growth references for breast-fed boys and girls: influence of breast-feeding and solids on growth until 36 months of age. Euro-Growth Study Group. J Pediatr Gastroenterol Nutr. 2000;31 Suppl 1:S60-71. | Independent variable
898 | Haschke, F.,Vanura, H.,Male, C.,Owen, G.,Pietschnig, B.,Schuster, E.,Krobath, E.,Huemer, C. Iron nutrition and growth of breast- and formula-fed infants during the first 9 months of life. J Pediatr Gastroenterol Nutr. 1993;16(2):151-6. | Group size
899 | Haschke, F.,Ziegler, E. E.,Grathwohl, D. Fast growth of infants of overweight mothers: Can it be slowed down?. Annals of Nutrition and Metabolism. 2014;64:19-24. | Independent variable
900 | Hasselbalch, H.,Jeppesen, D. L.,Ersboll, A. K.,Engelmann, M. D.,Nielsen, M. B. Thymus size evaluated by sonography. A longitudinal study on infants during the first year of life. Acta Radiol. 1997;38(2):222-7. | Group size
901 | Hassiotou, F.,Geddes, D. T. Programming of appetite control during breastfeeding as a preventative strategy against the obesity epidemic. J Hum Lact. 2014;30(2):136-42. | Study design
902 | Hatano, S.,Aihara, K.,Nishi, Y.,Usui, T. Trace elements (copper, zinc, manganese, and selenium) in plasma and erythrocytes in relation to dietary intake during infancy. J Pediatr Gastroenterol Nutr. 1985;4(1):87-92. | Group size
903 | Hathcock, A.,Krause, K.,Viera, A. J.,Fuemmeler, B. F.,Lovelady, C.,Ostbye, T. Satiety responsiveness and the relationship between breastfeeding and weight status of toddlers of overweight and obese women. Matern Child Health J. 2014;18(4):1023-30. | Study design
904 | Hattab, F. N.,Al-Omari, M. A.,Angmar-Mansson, B.,Daoud, N. The prevalence of nursing caries in one-to-four-year-old children in Jordan. ASDC J Dent Child. 1999;66(1):53-8. | Study design
905 | Hauck, F. R.,Herman, S. M.,Donovan, M.,Iyasu, S.,Merrick Moore, C.,Donoghue, E.,Kirschner, R. H.,Willinger, M. Sleep environment and the risk of sudden infant death syndrome in an urban population: the Chicago Infant Mortality Study. Pediatrics. 2003;111(5 Pt 2):1207-14. | Included for systematic reviews not completed
906 | Hawkins, S. S.,Cole, T. J.,Law, C. An ecological systems approach to examining risk factors for early childhood overweight: findings from the UK Millennium Cohort Study. J Epidemiol Community Health. 2009;63(2):147-55. | Included for systematic reviews not completed
907 | Hawley, N. L.,Johnson, W.,Nu’usolia, O.,McGarvey, S. T. The contribution of feeding mode to obesogenic growth trajectories in American Samoan infants. Pediatr Obes. 2014;9(1):e1-e13. | Independent variable
908 | Hay, A. E.,Campbell, C. M. A. Volunteer counsellors for supporting breast feeding..Graffy J, Taylor J, Williams A et al. Randomised controlled trial of support from volunteer counsellors for mothers considering breast feeding. BMJ 2004;328:26. (3 January). BMJ: British Medical Journal (International Edition). 2004;328(7435):349-349 1p. | Study design
909 | Hay, D. F.,Pawlby, S.,Sharp, D.,Asten, P.,Mills, A.,Kumar, R. Intellectual problems shown by 11-year-old children whose mothers had postnatal depression. J Child Psychol Psychiatry. 2001;42(7):871-89. | Included for systematic reviews not completed
910 | Hayatbakhsh, M. R.,O’Callaghan M, J.,Bor, W.,Williams, G. M.,Najman, J. M. Association of breastfeeding and adolescents’ psychopathology: A large prospective study. Breastfeeding Medicine. 2012;7(6):480-486. | Included for systematic reviews not completed
911 | Hayes, K. C.,Pronczuk, A.,Wood, R. A.,Guy, D. G. Modulation of infant formula fat profile alters the low-density lipoprotein/high-density lipoprotein ratio and plasma fatty acid distribution relative to those with breast-feeding. J Pediatr. 1992;120(4 Pt 2):S109-16. | Group size
912 | Hayosh, O.,Mandel, D.,Mimouni, F. B.,Lahat, S.,Marom, R.,Lubetzky, R. Prolonged duration of breastfeeding does not affect lipid profile in adulthood. Breastfeed Med. 2015;10(4):218-21. | Study design
913 | Hearst, Mary O.,Martin, Lauren,Rafdal, Brooke H.,Robinson, Ronel,McConnell, Scott R. Early childhood development and obesity risk-factors in a multi-ethnic, low-income community: Feasibility of the ‘Five Hundred under Five’ social determinants of health pilot study. Health Education Journal. 2013;72(2):203-215 13p. | Study design
914 | Heath, A. L.,Tuttle, C. R.,Simons, M. S.,Cleghorn, C. L.,Parnell, W. R. Longitudinal study of diet and iron deficiency anaemia in infants during the first two years of life. Asia Pac J Clin Nutr. 2002;11(4):251-7. | Independent variable
915 | Hedstrom, M. Breastfeeding and Amningshjalpen in Sweden. J Trop Pediatr. 1982;28(3):113-5. | Study design
916 | Hegde CV,Anand RK. Bowel pattern and weight gain in breastfed infants. Indian Pediatr. 1987;24:859-64. | Country
917 | Heikkila, K.,Kelly, Y.,Renfrew, M. J.,Sacker, A.,Quigley, M. A. Breastfeeding and educational achievement at age 5. Matern Child Nutr. 2014;10(1):92-101. | Included for systematic reviews not completed
918 | Heikkilä, K.,Sacker, A.,Kelly, Y.,Renfrew, M. J.,Quigley, M. A. 012 Breast feeding and behavioural development in children: findings from the Millennium Cohort Study. Journal of Epidemiology & Community Health. 2010;64:A5-A5 1p. | Peer review
919 | Heikkila, K.,Sacker, A.,Kelly, Y.,Renfrew, M. J.,Quigley, M. A. Breast feeding and child behaviour in the Millennium Cohort Study. Arch Dis Child. 2011;96(7):635-42. | Included for systematic reviews not completed
920 | Heine, W.,Lapsien, C. Influence of early breast milk and formula feeding on body weight in children born in Rostock since 1945. Bibl Nutr Dieta. 1982(31):17-8. | Study design, Independent variable
921 | Heiner, D. C. Modern research relating to food allergy and its implications--introduction. Clin Rev Allergy. 1984;2(1):1-5. | Study design
922 | Heinig, J.,Ishii, K. Exclusive breastfeeding: isn’t some breastfeeding good enough?. J Hum Lact. 2004;20(4):423-4. | Study design
923 | Heinig, M. J.,Nommsen, L. A.,Peerson, J. M.,Lonnerdal, B.,Dewey, K. G. Energy and protein intakes of breast-fed and formula-fed infants during the first year of life and their association with growth velocity: the DARLING Study. Am J Clin Nutr. 1993;58(2):152-61. | Independent variable
924 | Heinig, M. J.,Nommsen, L. A.,Peerson, J. M.,Lonnerdal, B.,Dewey, K. G. Intake and growth of breast-fed and formula-fed infants in relation to the timing of introduction of complementary foods: the DARLING study. Davis Area Research on Lactation, Infant Nutrition and Growth. Acta Paediatr. 1993;82(12):999-1006. | Independent variable
925 | Hemalatha, P.,Bhaskaram, P.,Kumar, P. A.,Khan, M. M.,Islam, M. A. Zinc status of breastfed and formula-fed infants of different gestational ages. J Trop Pediatr. 1997;43(1):52-4. | Country
926 | Henry, F. J.,Bartholomew, R. K. Epidemiology and transmission of rotavirus infections and diarrhoea in St. Lucia, West Indies. West Indian Med J. 1990;39(4):205-12. | Study design, Independent variable
927 | Heppe, D. H. M.,Kiefte-De Jong, J. C.,Durmuş, B.,Moll, H. A.,Raat, H.,Hofman, A.,Jaddoe, V. W. V. Parental, fetal, and infant risk factors for preschool overweight: The Generation R Study. Pediatric Research. 2013;73(1):120-127. | Included for systematic reviews not completed
928 | Hepworth, S. J.,Law, G. R.,Lawlor, D. A.,McKinney, P. A. Early life patterns of common infection: a latent class analysis. Eur J Epidemiol. 2010;25(12):875-83. | Included for systematic reviews not completed
929 | Herba, C. M.,Roza, S.,Govaert, P.,Hofman, A.,Jaddoe, V.,Verhulst, F. C.,Tiemeier, H. Breastfeeding and early brain development: the Generation R study. Matern Child Nutr. 2013;9(3):332-49. | Included for systematic reviews not completed
930 | Heresi, G.,Pizarro, F.,Olivares, M.,Cayazzo, M.,Hertrampf, E.,Walter, T.,Murphy, J. R.,Stekel, A. Effect of supplementation with an iron-fortified milk on incidence of diarrhea and respiratory infection in urban-resident infants. Scand J Infect Dis. 1995;27(4):385-9. | Included for systematic reviews not completed
931 | Hernell, O.,Lonnerdal, B. Iron status of infants fed low-iron formula: no effect of added bovine lactoferrin or nucleotides. Am J Clin Nutr. 2002;76(4):858-64. | Independent variable
932 | Hernell, O.,Lonnerdal, B. Nutritional evaluation of protein hydrolysate formulas in healthy term infants: plasma amino acids, hematology, and trace elements. Am J Clin Nutr. 2003;78(2):296-301. | Group size
933 | Hertrampf, E.,Cayazzo, M.,Pizarro, F.,Stekel, A. Bioavailability of iron in soy-based formula and its effect on iron nutriture in infancy. Pediatrics. 1986;78(4):640-5. | Independent variable
934 | Hide DW,Guyer BM. Cows milk intolerance in Isle of Wight infants. Br J Clin Pract. 1983;37:285-7. | Dependent variable
935 | Hide, D. W. Aspects of nutrition: Isle of Wight infant feeding survey. Health Visit. 1980;53(2):43. | Study design
936 | Hide, D. W. The clinical expression of allergy in breast-fed infants. Adv Exp Med Biol. 1991;310:475-80. | Study design
937 | Hide, D. W.,Guyer, B. M. Clinical manifestations of allergy related to breast and cows’ milk feeding. Arch Dis Child. 1981;56(3):172-5. | Independent variable
938 | Hide, D. W.,Guyer, B. M. Clinical manifestations of allergy related to breast- and cow’s milk-feeding. Pediatrics. 1985;76(6):973-5. | Independent variable
939 | Hide, D. W.,Matthews, S.,Matthews, L.,Stevens, M.,Ridout, S.,Twiselton, R.,Gant, C.,Arshad, S. H. Effect of allergen avoidance in infancy on allergic manifestations at age two years. J Allergy Clin Immunol. 1994;93(5):842-6. | Independent variable
940 | Hide, D. W.,Matthews, S.,Tariq, S.,Arshad, S. H. Allergen avoidance in infancy and allergy at 4 years of age. Allergy. 1996;51(2):89-93. | Independent variable
941 | Higashi, A.,Ikeda, T.,Uehara, I.,Matsuda, I. Effect of low-content zinc and copper formula on infant nutrition. Eur J Pediatr. 1982;138(3):237-40. | Group size
942 | Highet, A. R.,Berry, A. M.,Bettelheim, K. A.,Goldwater, P. N. Gut microbiome in sudden infant death syndrome (SIDS) differs from that in healthy comparison babies and offers an explanation for the risk factor of prone position. Int J Med Microbiol. 2014;304(5-6):735-41. | Independent variable, Dependent variable
943 | Hijazi, S. S.,Abulaban, A.,Waterlow, J. C. The duration for which exclusive breast-feeding is adequate. A study in Jordan. Acta Paediatr Scand. 1989;78(1):23-8. | Independent variable
944 | Hiley, C. M.,Morley, C. J. Risk factors for sudden infant death syndrome: further change in 1992-3. BMJ. 1996;312(7043):1397-8. | Study design
945 | Hill, D. J.,Hosking, C. S. Preventing childhood allergy. Med J Aust. 1993;158(6):367-9. | Study design
946 | Hillman, L. S. Bone mineral content in term infants fed human milk, cow milk-based formula, or soy-based formula. J Pediatr. 1988;113(1 Pt 2):208-12. | Group size
947 | Hillman, L. S.,Chow, W.,Salmons, S. S.,Weaver, E.,Erickson, M.,Hansen, J. Vitamin D metabolism, mineral homeostasis, and bone mineralization in term infants fed human milk, cow milk-based formula, or soy-based formula. J Pediatr. 1988;112(6):864-74. | Group size
948 | Hirota, T.,Nara, M.,Ohguri, M.,Manago, E.,Hirota, K. Effect of diet and lifestyle on bone mass in Asian young women. Am J Clin Nutr. 1992;55(6):1168-73. | Study design
949 | Hitchcock, N. E.,Coy, J. F. The growth of healthy Australian infants in relation to infant feeding and social group. Med J Aust. 1989;150(6):306-8, 310-1. | Included for systematic reviews not completed
950 | Hitchcock, N. E.,Gracey, M.,Gilmour, A. I. The growth of breast fed and artificially fed infants from birth to twelve months. Acta Paediatr Scand. 1985;74(2):240-5. | Included for systematic reviews not completed
951 | Hitchcock, N. E.,Gracey, M.,Owles, E. N. Growth of healthy breast-fed infants in the first six months. Lancet. 1981;2(8237):64-5. | Study design, Independent variable
952 | Hitchcock, N. E.,McGuiness, D.,Gracey, M. Growth and feeding practices of Western Australian infants. Med J Aust. 1982;1(9):372-6. | Included for systematic reviews not completed
953 | Hitchcock, N. E.,Owles, E. N.,Gracey, M. Breast feeding and growth of healthy infants. Med J Aust. 1981;2(10):536-7. | Study design
954 | Hoffhines, H.,Whaley, K. D.,Blackett, P. R.,Palumbo, K.,Campbell-Sternloff, D.,Glore, S.,Lee, E. T. Early childhood nutrition in an American Indian community: educational strategy for obesity prevention. J Okla State Med Assoc. 2014;107(2):55-9. | Dependent variable
955 | Hoffmans, M. D.,Obermann-de Boer, G. L.,Florack, E. I.,van Kampen-Donker, M.,Kromhout, D. Determinants of growth during early infancy. Hum Biol. 1988;60(2):237-49. | Included for systematic reviews not completed
956 | Hofvander Y,Hillervik C. Breast-feeding in Swedish hospitals. World Health Forum. 1995;16:95-9. | Study design, Dependent variable
957 | Hogendorf, A.,Stanczyk-Przyluska, A.,Sieniwicz-Luzenczyk, K.,Wiszniewska, M.,Arendarczyk, J.,Banasik, M.,Fendler, W.,Kowalski, M.,Zeman, K. Is there any association between secretory IgA and lactoferrin concentration in mature human milk and food allergy in breastfed children. Med Wieku Rozwoj. 2013;17(1):47-52. | Independent variable
958 | Hokama, T. A study of the hemoglobin levels in breast-fed infants in one village of Okinawa prefecture. Acta Paediatr Jpn. 1993;35(2):138-40. | Group size
959 | Hokama, T. Levels of serum ferritin and total body iron among infants with different feeding regimens. Acta Paediatr Jpn. 1993;35(4):298-301. | Study design
960 | Hokama, T.,Sakamoto, R.,Yara, A.,Asato, Y.,Takamine, F.,Itokazu, K. Incidence of Haemophilus influenzae in the throats of healthy infants with different feeding methods. Pediatr Int. 1999;41(3):277-80. | Study design
961 | Holberg, C. J.,Wright, A. L.,Martinez, F. D.,Ray, C. G.,Taussig, L. M.,Lebowitz, M. D. Risk factors for respiratory syncytial virus-associated lower respiratory illnesses in the first year of life. Am J Epidemiol. 1991;133(11):1135-51. | Independent variable
962 | Holland, B. Breast-feeding, social variables, and infant mortality: a hazards model analysis of the case of Malaysia. Soc Biol. 1987;34(1-2):78-93. | Study design
963 | Holland, B. The validity of retrospective breast-feeding-duration data: an illustrative analysis of data quality in the Malaysian Family Life Survey. Hum Biol. 1987;59(3):477-87. | Study design
964 | Hollen, L. I.,Din, Zu,Jones, L. R.,Emond, A. M.,Emmett, P. Are diet and feeding behaviours associated with the onset of and recovery from slow weight gain in early infancy?. Br J Nutr. 2014;111(9):1696-704. | Independent variable
965 | Holm, A. K.,Andersson, R. Enamel mineralization disturbances in 12-year-old children with known early exposure to fluorides. Community Dent Oral Epidemiol. 1982;10(6):335-9. | Dependent variable
966 | Holman, D. J.,Yamaguchi, K. Longitudinal analysis of deciduous tooth emergence: IV. Covariate effects in Japanese children. Am J Phys Anthropol. 2005;126(3):352-8. | Independent variable
967 | Holme, A.,MacArthur, C.,Lancashire, R. The effects of breastfeeding on cognitive and neurological development of children at 9 years. Child Care Health Dev. 2010;36(4):583-90. | Study design
968 | Holmes, G. E.,Hassanein, K. M.,Miller, H. C. Factors associated with infections among breast-fed babies and babies fed proprietary milks. Pediatrics. 1983;72(3):300-6. | Independent variable
969 | Holmes, V. A.,Cardwell, C.,McKinley, M. C.,Young, I. S.,Murray, L. J.,Boreham, C. A.,Woodside, J. V. Association between breast-feeding and anthropometry and CVD risk factor status in adolescence and young adulthood: the Young Hearts Project, Northern Ireland. Public Health Nutr. 2010;13(6):771-8. | Independent variable
970 | Holscher, H. D.,Czerkies, L. A.,Cekola, P.,Litov, R.,Benbow, M.,Santema, S.,Alexander, D. D.,Perez, V.,Sun, S.,Saavedra, J. M.,Tappenden, K. A. Bifidobacterium lactis Bb12 enhances intestinal antibody response in formula-fed infants: a randomized, double-blind, controlled trial. JPEN J Parenter Enteral Nutr. 2012;36(1 Suppl):106S-17S. | Independent variable
971 | Holt, R. D.,Joels, D.,Winter, G. B. Caries in pre-school children. The Camden study. Br Dent J. 1982;153(3):107-9. | Study design
972 | Holt, R. D.,Winter, G. B.,Downer, M. C.,Bellis, W. J.,Hay, I. S. Caries in pre-school children in Camden 1993/94. Br Dent J. 1996;181(11-12):405-10. | Study design
973 | Hon, K. L. E.,Leung, T. F.,Kam, W. Y. C.,Lam, M. C. A.,Fok, T. F.,Ng, P. C. Dietary restriction and supplementation in children with atopic eczema. Clinical and Experimental Dermatology. 2006;31(2):187-191. | Study design
974 | Hong, L.,Levy, S. M.,Warren, J. J.,Broffitt, B. Infant breast-feeding and childhood caries: a nine-year study. Pediatr Dent. 2014;36(4):342-7. | Included for systematic reviews not completed
975 | Hong, X.,Wang, G.,Liu, X.,Kumar, R.,Tsai, H. J.,Arguelles, L.,Hao, K.,Pearson, C.,Ortiz, K.,Bonzagni, A.,Apollon, S.,Fu, L.,Caruso, D.,Pongracic, J. A.,Schleimer, R.,Holt, P. G.,Bauchner, H.,Wang, X. Gene polymorphisms, breast-feeding, and development of food sensitization in early childhood. J Allergy Clin Immunol. 2011;128(2):374-81 e2. | Dependent variable
976 | Hong, Z. Y.,Zhang, Y. W.,Xu, J. D.,Zhou, J. D.,Gao, X. L.,Liu, X. G.,Shi, Y. Y. Growth promoting effect of zinc supplementation in infants of high-risk pregnancies. Chin Med J (Engl). 1992;105(10):844-8. | Group size
977 | Honorio, R. F.,Costa Monteiro Hadler, M. C. Factors associated with obesity in brazilian children enrolled in the school health program: a case-control study. Nutr Hosp. 2014;30(3):526-34. | Included for systematic reviews not completed
978 | Hopkins, D.,Emmett, P.,Steer, C.,Rogers, I.,Noble, S.,Emond, A. Infant feeding in the second 6 months of life related to iron status: an observational study. Arch Dis Child. 2007;92(10):850-4. | Independent variable
979 | Hopkins, D.,Steer, C. D.,Northstone, K.,Emmett, P. M. Effects on childhood body habitus of feeding large volumes of cow or formula milk compared with breastfeeding in the latter part of infancy. Am J Clin Nutr. 2015;102(5):1096-103. | Independent variable
980 | Hopkinson, J. Is it possible for a breastfed baby to be overweight?. J Hum Lact. 2003;19(2):189-90. | Study design
981 | Hoppu, U.,Kalliomaki, M.,Isolauri, E. Cow’s milk allergy--a matter of fat. Allergy. 2002;57(1):61-2. | Study design, Independent variable
982 | Horby Jorgensen, M.,Holmer, G.,Lund, P.,Hernell, O.,Michaelsen, K. F. Effect of formula supplemented with docosahexaenoic acid and gamma-linolenic acid on fatty acid status and visual acuity in term infants. J Pediatr Gastroenterol Nutr. 1998;26(4):412-21. | Independent variable
983 | Horst, C. H.,Obermann-de Boer, G. L.,Kromhout, D. Type of milk feeding and nutrient intake during infancy. The Leiden Pre-School Children Study. Acta Paediatr Scand. 1987;76(6):865-71. | Study design, Dependent variable
984 | Horta, B. L.,Bas, A.,Bhargava, S. K.,Fall, C. H.,Feranil, A.,de Kadt, J.,Martorell, R.,Richter, L. M.,Stein, A. D.,Victora, C. G. Infant feeding and school attainment in five cohorts from low- and middle-income countries. PLoS One. 2013;8(8):e71548. | Included for systematic reviews not completed
985 | Horton, C. An overview of the NUTRIMENTHE project. Nutrition Bulletin. 2012;37(2):152-156 5p. | Study design
986 | Horwood, L. J.,Fergusson, D. M. Breastfeeding and later cognitive and academic outcomes. Pediatrics. 1998;101(1):E9. | Included for systematic reviews not completed
987 | Horwood, L. J.,Fergusson, D. M.,Shannon, F. T. Social and familial factors in the development of early childhood asthma. Pediatrics. 1985;75(5):859-68. | Independent variable
988 | Hosseini, S. M.,Maracy, M. R.,Sarrafzade, S.,Kelishadi, R. Child weight growth trajectory and its determinants in a sample of Iranian children from birth until 2 years of age. International Journal of Preventive Medicine. 2014;5(3):348-355. | Independent variable
989 | Host, A.,Husby, S.,Osterballe, O. A prospective study of cow’s milk allergy in exclusively breast-fed infants. Incidence, pathogenetic role of early inadvertent exposure to cow’s milk formula, and characterization of bovine milk protein in human milk. Acta Paediatr Scand. 1988;77(5):663-70. | Study design, Independent variable
990 | Houston M,Howie P,McNeilly A. Nursing Mirror Midwifery Forum 4. Infant feeding. Nurs Mirror. 1983;156:i-iv. | Study design
991 | Howe, L. D.,Ellison-Loschmann, L.,Pearce, N.,Douwes, J.,Jeffreys, M.,Firestone, R. Ethnic differences in risk factors for obesity in New Zealand infants. J Epidemiol Community Health. 2015;69(6):516-22. | Independent variable, Dependent variable
992 | Howie, P. W.,Forsyth, J. S.,Ogston, S. A.,Clark, A.,Florey, C. D. Protective effect of breast feeding against infection. BMJ. 1990;300(6716):11-6. | Included for systematic reviews not completed
993 | Howie, P. W.,Forsyth, J. S.,Ogston, S. A.,Clark, A.,Florey, C. Protective effect of breastfeeding against infection.. this article originally appeared in the British Medical Journal, V. 300. Reproduced with permission. Breastfeeding Review. 1990;2(1):7-15 9p. | Included for systematic reviews not completed
994 | Hoyle, B.,Yunus, M.,Chen, L. C. Breast-feeding and food intake among children with acute diarrheal disease. The American journal of clinical nutrition. 1980;33(11):2365-2371. | Study design, Country
995 | Hromadova, M.,Kostalova, L.,Leskova, L.,Kapellerova, A. Relationship between the duration of the breast-feeding period and the lipoprotein profile of children at the age of 13 years. Physiol Res. 1997;46(1):21-5. | Group size
996 | Huang, D. Y.,Lanza, H. I.,Anglin, M. D. Trajectory of Adolescent Obesity: Exploring the Impact of Prenatal to Childhood Experiences. J Child Fam Stud. 2014;23(6):1090-1101. | Included for systematic reviews not completed
997 | Huang, J.,Peters, K. E.,Vaughn, M. G.,Witko, C. Breastfeeding and trajectories of children’s cognitive development. Dev Sci. 2014;17(3):452-61. | Included for systematic reviews not completed
998 | Huang, J.,Vaughn, M. G.,Kremer, K. P. Breastfeeding and child development outcomes: an investigation of the nurturing hypothesis. Matern Child Nutr. 2015. | Included for systematic reviews not completed
999 | Huang, R. C.,Mori, T. A.,Beilin, L. J. Early life programming of cardiometabolic disease in the Western Australian pregnancy cohort (Raine) study. Clinical and Experimental Pharmacology and Physiology. 2012;39(11):973-978. | Study design
1000 | Huffman, S. L.,Dewey, K. G.,Schofield, D. Moving ahead with maternal, infant, and young child nutrition: need to integrate actions. Food Nutr Bull. 2010;31(2 Suppl):S99. | Study design
1001 | Huffman, S. L.,Lopez de Romana, G.,Madrid, S.,Brown, K. H.,Bentley, M.,Black, R. E. Do child feeding practices change due to diarrhoea in the Central Peruvian Highlands?. J Diarrhoeal Dis Res. 1991;9(4):295-300. | Study design, Dependent variable
1002 | Huh, S. Y.,Rifas-Shiman, S. L.,Taveras, E. M.,Oken, E.,Gillman, M. W. Timing of solid food introduction and risk of obesity in preschool-aged children. Pediatrics. 2011;127(3):e544-51. | Independent variable
1003 | Hummel, M.,Fuchtenbusch, M.,Schenker, M.,Ziegler, A. G. No major association of breast-feeding, vaccinations, and childhood viral diseases with early islet autoimmunity in the German BABYDIAB Study. Diabetes Care. 2000;23(7):969-74. | Dependent variable
1004 | Hummel, S.,Pfluger, M.,Kreichauf, S.,Hummel, M.,Ziegler, A. G. Predictors of overweight during childhood in offspring of parents with type 1 diabetes. Diabetes Care. 2009;32(5):921-5. | Included for systematic reviews not completed
1005 | Hundt, G. A.,Forman, M. R. Interfacing anthropology and epidemiology: the Bedouin Arab Infant Feeding Study. Soc Sci Med. 1993;36(7):957-64. | Study design, Dependent variable
1006 | Hutchison, B. L.,Thompson, J. M.,Mitchell, E. A. Infant care practices related to sudden unexpected death in infancy: a 2013 survey. N Z Med J. 2015;128(1408):15-22. | Study design, Dependent variable
1007 | Huttunen, J. K.,Saarinen, U. M.,Kostiainen, E.,Siimes, M. A. Fat composition of the infant diet does not influence subsequent serum lipid levels in man. Atherosclerosis. 1983;46(1):87-94. | Independent variable
1008 | Huurre, A.,Laitinen, K.,Rautava, S.,Korkeamaki, M.,Isolauri, E. Impact of maternal atopy and probiotic supplementation during pregnancy on infant sensitization: a double-blind placebo-controlled study. Clin Exp Allergy. 2008;38(8):1342-8. | Dependent variable
1009 | Huus, K.,Ludvigsson, J. F.,Enskar, K.,Ludvigsson, J. Exclusive breastfeeding of Swedish children and its possible influence on the development of obesity: a prospective cohort study. BMC Pediatr. 2008;8:42. | Included for systematic reviews not completed
1010 | Huybrechts, I.,De Vriendt, T.,Breidenassel, C.,Rogiers, J.,Vanaelst, B.,Cuenca-Garcia, M.,Moreno, L. A.,Gonzalez-Gross, M.,Roccaldo, R.,Kafatos, A.,Clays, E.,Bueno, G.,Beghin, L.,Sjostrom, M.,Manios, Y.,Molnar, D.,Pisa, P. T.,De Henauw, S. Mechanisms of stress, energy homeostasis and insulin resistance in European adolescents--the HELENA study. Nutr Metab Cardiovasc Dis. 2014;24(10):1082-9. | Study design
1011 | Hwang, J. B.,Lee, S. H.,Kang, Y. N.,Kim, S. P.,Suh, S. I.,Kam, S. Indexes of suspicion of typical cow’s milk protein-induced enterocolitis. J Korean Med Sci. 2007;22(6):993-7. | Independent variable, Health status
1012 | Hyland, F. Breastfeeding: for those who won’t. Community Outlook. 1988:11-2. | Study design
1013 | Hysing, M.,Harvey, A. G.,Torgersen, L.,Ystrom, E.,Reichborn-Kjennerud, T.,Sivertsen, B. Trajectories and predictors of nocturnal awakenings and sleep duration in infants. J Dev Behav Pediatr. 2014;35(5):309-16. | Dependent variable
1014 | Iacono, G.,Merolla, R.,D’Amico, D.,Bonci, E.,Cavataio, F.,Di Prima, L.,Scalici, C.,Indinnimeo, L.,Averna, M. R.,Carroccio, A. Gastrointestinal symptoms in infancy: a population-based prospective study. Dig Liver Dis. 2005;37(6):432-8. | Independent variable, Dependent variable
1015 | Iannotti, L. L.,Zavaleta, N.,León, Z.,Caulfield, E. L. Growth and body composition of Peruvian infants in a peri urban setting. Food and Nutrition Bulletin. 2009;30(3):245-253. | Independent variable
1016 | Imai, C. M.,Gunnarsdottir, I.,Thorisdottir, B.,Halldorsson, T. I.,Thorsdottir, I. Associations between infant feeding practice prior to six months and body mass index at six years of age. Nutrients. 2014;6(4):1608-17. | Independent variable
1017 | Immunology of milk and the neonate. Adv Exp Med Biol. 1991;310:1-480. | Study design
1018 | Inamo, Y.,Hasegawa, M.,Saito, K.,Hayashi, R.,Ishikawa, T.,Yoshino, Y.,Hashimoto, K.,Fuchigami, T. Serum vitamin D concentrations and associated severity of acute lower respiratory tract infections in Japanese hospitalized children. Pediatr Int. 2011;53(2):199-201. | Study design
1019 | Inanç, B. B.,Şahin, D. S.,Oǧuzüncül, A. F.,Bindak, R.,Mungan, F. Prevalence of obesity in elementary schools in mardin, south-eastern of turkey: A preliminary study. Balkan Medical Journal. 2012;29(4):424-430. | Study design
1020 | Infant feeding practices and their possible relationship to the etiology of diabetes mellitus. American Academy of Pediatrics Work Group on Cow’s Milk Protein and Diabetes Mellitus. Pediatrics. 1994;94(5):752-4. | Study design
1021 | Innis, S. M. Human milk and formula fatty acids. J Pediatr. 1992;120(4 Pt 2):S56-61. | Study design, Dependent variable
1022 | Innis, S. M.,Auestad, N.,Siegman, J. S. Blood lipid docosahexaenoic and arachidonic acid in term gestation infants fed formulas with high docosahexaenoic acid, low eicosapentaenoic acid fish oil. Lipids. 1996;31(6):617-25. | Group size
1023 | Innis, S. M.,Diersen-Schade, D. A.,Akrabawi, S. S. Prospective evaluation of preferential looking acuity in healthy term infants fed infant formula or breast fed. Pediatric research. 1995;37(4):308a. | Peer review
1024 | Innis, S. M.,Friesen, R. W. Maternal DHA supplementation in pregnancy: a double blind randomized prospective trial of maternal N-3 fatty acid status, human milk fatty acids and infant development. Pediatric Academic Societies Annual Meeting; 2007 May 5-8; Toronto, Canada. 2007. | Peer review
1025 | Innis, S. M.,Nelson, C. M.,Lwanga, D.,Rioux, F. M.,Waslen, P. Feeding formula without arachidonic acid and docosahexaenoic acid has no effect on preferential looking acuity or recognition memory in healthy full-term infants at 9 mo of age. Am J Clin Nutr. 1996;64(1):40-6. | Study design, Independent variable
1026 | Inostroza, J.,Haschke, F.,Steenhout, P.,Grathwohl, D.,Nelson, S. E.,Ziegler, E. E. Low-protein formula slows weight gain in infants of overweight mothers. J Pediatr Gastroenterol Nutr. 2014;59(1):70-7. | Included for systematic reviews not completed
1027 | Iron-Segev, S.,Peterson, K. E.,Gillman, M. W.,Williams, C. M.,Austin, S. B.,Field, A. E. Associations of breastfeeding with bulimic behaviors and eating disorders among adolescents. Int J Eat Disord. 2013;46(8):834-40. | Dependent variable
1028 | Isaacs, C. E.,Jia, J. H. The anti-infective activity of human milk is potentially greater than the sum of its microbicidal components. Adv Exp Med Biol. 2004;554:439-41. | Study design, Dependent variable
1029 | Isaacs, E. B.,Fischl, B. R.,Quinn, B. T.,Chong, W. K.,Gadian, D. G.,Lucas, A. Impact of breast milk on intelligence quotient, brain size, and white matter development. Pediatr Res. 2010;67(4):357-62. | Health status
1030 | Islam, M. A.,Rahman, M. M.,Mahalanabis, D. Maternal and socioeconomic factors and the risk of severe malnutrition in a child: a case-control study. Eur J Clin Nutr. 1994;48(6):416-24. | Country
1031 | Islam, M. A.,Rahman, M. M.,Mahalanabis, D.,Rahman, A. K. Death in a diarrhoeal cohort of infants and young children soon after discharge from hospital: risk factors and causes by verbal autopsy. J Trop Pediatr. 1996;42(6):342-7. | Country
1032 | Isolauri, E. Nutrition, allergy, mucosal immunology and intestinal microbiota: the effects of maternal nutrition during pregnancy and breast feeding on the risk of allergic disease. ClinicalTrials.gov [http://clinicaltrials.gov]. 2005. | Peer review
1033 | Isomura, H.,Takimoto, H.,Miura, F.,Kitazawa, S.,Takeuchi, T.,Itabashi, K.,Kato, N.. Type of milk feeding affects hematological parameters and serum lipid profile in Japanese infants. Pediatr Int. 2011;53(6):807-13. | Included for systematic reviews not completed
1034 | Ito, J.,Fujiwara, T. Breastfeeding and risk of atopic dermatitis up to the age 42 months: a birth cohort study in Japan. Ann Epidemiol. 2014;24(4):267-72. | Independent variable
1035 | Ivanovic, D.,Ivanovic, R.,Buitron, C. Nutritional status, birth weight and breast feeding of elementary first grade Chilean students. Nutrition Reports International. 1987;36(6):1347-1361. | Study design
1036 | Ivarsson, A.,Persson, L. A.,Nystrom, L.,Ascher, H.,Cavell, B.,Danielsson, L.,Dannaeus, A.,Lindberg, T.,Lindquist, B.,Stenhammar, L.,Hernell, O. Epidemic of coeliac disease in Swedish children. Acta Paediatr. 2000;89(2):165-71. | Study design, Independent variable
1037 | Izadi, V.,Kelishadi, R.,Qorbani, M.,Esmaeilmotlagh, M.,Taslimi, M.,Heshmat, R.,Ardalan, G.,Azadbakht, L. Duration of breast-feeding and cardiovascular risk factors among Iranian children and adolescents: the CASPIAN III study. Nutrition. 2013;29(5):744-51. | Study design
1038 | J. M, Hamid Jan,Mitra, Amal K.,H, Hasmiza,C. D, Pim,L. O, Ng,W. M, Wan Manan. Effect of Gender and Nutritional Status on Academic Achievement and Cognitive Function among Primary School Children in a Rural District in Malaysia. Malaysian Journal of Nutrition. 2011;17(2):189-200 12p. | Study design
1039 | Jaber, L. Preventive intervention for iron deficiency anaemia in a high risk population. Int J Risk Saf Med. 2014;26(3):155-62. | Included for systematic reviews not completed
1040 | Jackson, D. B.,Beaver, K. M. The Association Between Breastfeeding Exposure and Duration, Neuropsychological Deficits, and Psychopathic Personality Traits in Offspring: The Moderating Role of 5HTTLPR. Psychiatr Q. 2015. | Included for systematic reviews not completed
1041 | Jackson, J. M.,Mourino, A. P. Pacifier use and otitis media in infants twelve months of age or younger. Pediatr Dent. 1999;21(4):255-60. | Study design
1042 | Jacobson, J. L.,Jacobson, S. W. Association of prenatal exposure to an environmental contaminant with intellectual function in childhood. J Toxicol Clin Toxicol. 2002;40(4):467-75. | Group size
1043 | Jacobson, S. W.,Chiodo, L. M.,Jacobson, J. L. Breastfeeding effects on intelligence quotient in 4- and 11-year-old children. Pediatrics. 1999;103(5):e71. | Included for systematic reviews not completed
1044 | Jacoby, P.,Carville, K. S.,Hall, G.,Riley, T. V.,Bowman, J.,Leach, A. J.,Lehmann, D. Crowding and other strong predictors of upper respiratory tract carriage of otitis media-related bacteria in Australian Aboriginal and non-Aboriginal children. Pediatr Infect Dis J. 2011;30(6):480-5. | Dependent variable
1045 | Jaganath, D.,Saito, M.,Gilman, R. H.,Queiroz, D. M.,Rocha, G. A.,Cama, V.,Cabrera, L.,Kelleher, D.,Windle, H. J.,Crabtree, J. E.,Checkley, W. First detected Helicobacter pylori infection in infancy modifies the association between diarrheal disease and childhood growth in Peru. Helicobacter. 2014;19(4):272-9. | Independent variable, Dependent variable
1046 | Jain, L. Our babies are what we feed them. Clin Perinatol. 2014;41(2):xv-xvii. | Study design
1047 | Jain, M. K.,Vora, J. N.,Kale, V. V.,Iyyer, L.,Irani, S. F. A study of non-epidemic diarrhea in the newborns. Indian Pediatr. 1984;21(1):56-60. | Country
1048 | Jain, R.,Acharya, A. S. Supplemental folic acid in pregnancy and childhood asthma. Natl Med J India. 2010;23(6):351-2. | Study design
1049 | Jalevik, B.,Noren, J. G.,Klingberg, G.,Barregard, L. Etiologic factors influencing the prevalence of demarcated opacities in permanent first molars in a group of Swedish children. Eur J Oral Sci. 2001;109(4):230-4. | Study design
1050 | James, J.,Evans, J.,Male, P.,Pallister, C.,Hendrikz, J. K.,Oakhill, A. Iron deficiency in inner city pre-school children: development of a general practice screening programme. J R Coll Gen Pract. 1988;38(311):250-2. | Study design
1051 | James, M. Child’s nutritional needs: nature’s wonderful formula. Nurs J India. 1986;77(7):180-1, 196. | Study design
1052 | Janevic, T.,Petrovic, O.,Bjelic, I.,Kubera, A. Risk factors for childhood malnutrition in Roma settlements in Serbia. BMC Public Health. 2010;10:509. | Study design
1053 | Janowitz, B.,Nichols, D. J. Child survivorship and pregnancy spacing in Iran. J Biosoc Sci. 1983;15(1):35-46. | Dependent variable
1054 | Jansen, A. A. Malnutrition and child feeding practices in the Kingdom of Tonga. J Trop Pediatr. 1982;28(4):202-8. | Study design
1055 | Jansen, H.,Huiting, H. G.,Scholtens, S.,Sauer, P. J.,Stolk, R. P. HbA1c in nondiabetic Dutch infants aged 8-12 months: the GECKO-Drenthe birth cohort study. Diabetes Care. 2011;34(2):403-5. | Study design
1056 | Jansen, M. A.,Tromp, II,Kiefte-de Jong, J. C.,Jaddoe, V. W.,Hofman, A.,Escher, J. C.,Hooijkaas, H.,Moll, H. A. Infant feeding and anti-tissue transglutaminase antibody concentrations in the Generation R Study. Am J Clin Nutr. 2014;100(4):1095-101. | Dependent variable
1057 | Jarvisalo, M. J.,Hutri-Kahonen, N.,Juonala, M.,Mikkila, V.,Rasanen, L.,Lehtimaki, T.,Viikari, J.,Raitakari, O. T. Breast feeding in infancy and arterial endothelial function later in life. The Cardiovascular Risk in Young Finns Study. Eur J Clin Nutr. 2009;63(5):640-5. | Independent variable
1058 | Javed, A.,Yoo, K. H.,Agarwal, K.,Jacobson, R. M.,Li, X.,Juhn, Y. J. Characteristics of children with asthma who achieved remission of asthma. J Asthma. 2013;50(5):472-9. | Health status
1059 | Jedrychowski, W.,Maugeri, U.,Perera, F.,Stigter, L.,Jankowski, J.,Butscher, M.,Mroz, E.,Flak, E.,Skarupa, A.,Sowa, A. Cognitive function of 6-year old children exposed to mold-contaminated homes in early postnatal period. Prospective birth cohort study in Poland. Physiol Behav. 2011;104(5):989-95. | Independent variable
1060 | Jedrychowski, W.,Perera, F.,Jankowski, J.,Butscher, M.,Mroz, E.,Flak, E.,Kaim, I.,Lisowska-Miszczyk, I.,Skarupa, A.,Sowa, A. Effect of exclusive breastfeeding on the development of children’s cognitive function in the Krakow prospective birth cohort study. Eur J Pediatr. 2012;171(1):151-8. | Independent variable
1061 | Jelding-Dannemand, E.,Malby Schoos, A. M.,Bisgaard, H. Breast-feeding does not protect against allergic sensitization in early childhood and allergy-associated disease at age 7 years. J Allergy Clin Immunol. 2015;136(5):1302-1308 e13. | Independent variable
1062 | Jelliffe DB. Recent developments in breastfeeding. Med J Malaysia. 1986;41:59-63. | Study design
1063 | Jelliffee, E. F. Breastfeeding and the prevention of malnutrition. Med J Malaysia. 1986;41(1):88-92. | Study design
1064 | Jenkins, A. L.,Gyorkos, T. W.,Joseph, L.,Culman, K. N.,Ward, B. J.,Pekeles, G. S.,Mills, E. L. Risk factors for hospitalization and infection in Canadian Inuit infants over the first year of life--a pilot study. Int J Circumpolar Health. 2004;63(1):61-70. | Group size
1065 | Jenkins, J. M.,Foster, E. M. The effects of breastfeeding exclusivity on early childhood outcomes. Am J Public Health. 2014;104 Suppl 1:S128-35. | Included for systematic reviews not completed
1066 | Jensen, B. H.,Röser, D.,Andreassen, B. U.,Olsen, K. E. P.,Nielsen, H. V.,Roldgaard, B. B.,Schjørring, S.,Mirsepasi-Lauridsen, H. C.,Jørgensen, S. L.,Mortensen, E. M.,Petersen, A. M.,Krogfelt, K. A. Childhood diarrhoea in Danish day care centres could be associated with infant colic, low birthweight and antibiotics. Acta Paediatrica, International Journal of Paediatrics. 2015. | Independent variable
1067 | Jensen, C. L.,Prager, T. C.,Fraley, J. K.,Chen, H.,Anderson, R. E.,Heird, W. C. Effect of dietary linoleic/alpha-linolenic acid ratio on growth and visual function of term infants. J Pediatr. 1997;131(2):200-9. | Independent variable
1068 | Jensen, C. L.,Prager, T. C.,Zou, Y.,Fraley, J. K.,Maude, M.,Anderson, R. E.,Heird, W. C. Effects of maternal docosahexaenoic acid supplementation on visual function and growth of breast-fed term infants. Lipids. 1999;34 Suppl:S225. | No full text
1069 | Jensen, E. T.,Kappelman, M. D.,Kim, H. P.,Ringel-Kulka, T.,Dellon, E. S. Early life exposures as risk factors for pediatric eosinophilic esophagitis. J Pediatr Gastroenterol Nutr. 2013;57(1):67-71. | Dependent variable
1070 | Jensen, S. M.,Ritz, C.,Ejlerskov, K. T.,Molgaard, C.,Michaelsen, K. F. Infant BMI peak, breastfeeding, and body composition at age 3 y. Am J Clin Nutr. 2015;101(2):319-25. | Dependent variable
1071 | Jensen, T. K.,Grandjean, P.,Jorgensen, E. B.,White, R. F.,Debes, F.,Weihe, P. Effects of breast feeding on neuropsychological development in a community with methylmercury exposure from seafood. J Expo Anal Environ Epidemiol. 2005;15(5):423-30. | Included for systematic reviews not completed
1072 | Jeris, L. S.,Thies, P. A. Infant feeding practices and dental health. Part 1: the biological specificity of human milk. Bull Mich Dent Hyg Assoc. 1980;10(3):9-10. | Study design
1073 | Jiang, M.,Foster, E. M. Duration of breastfeeding and childhood obesity: a generalized propensity score approach. Health Serv Res. 2013;48(2 Pt 1):628-51. | Included for systematic reviews not completed
1074 | Jiang, M.,Foster, E. M.,Gibson-Davis, C. M. Breastfeeding and the child cognitive outcomes: a propensity score matching approach. Matern Child Health J. 2011;15(8):1296-307. | Included for systematic reviews not completed
1075 | Jin, C.,MacKay Rossignol, A. Effects of passive smoking on respiratory illness from birth to age eighteen months, in Shanghai, People’s Republic of China. Journal of Pediatrics. 1993;123(4):553-558. | Study design, Independent variable
1076 | Jin, H. J.,Lee, J. H.,Kim, M. K. The prevalence of vitamin D deficiency in iron-deficient and normal children under the age of 24 months. Blood Research. 2013;48(1):40-45. | Study design
1077 | Jing, H.,Gilchrist, J. M.,Badger, T. M.,Pivik, R. T. A longitudinal study of differences in electroencephalographic activity among breastfed, milk formula-fed, and soy formula-fed infants during the first year of life. Early Hum Dev. 2010;86(2):119-25. | Included for systematic reviews not completed
1078 | Jing, H.,Pivik, R. T.,Dykman, R. A.,Gilchrist, J. M.,Badger, T. M. Effects of breast milk and milk formula diets on synthesized speech sound-induced event-related potentials in 3- and 6-month-old infants. Dev Neuropsychol. 2007;31(3):349-62. | Group size
1079 | Jing, H.,Xu, H.,Wan, J.,Yang, Y.,Ding, H.,Chen, M.,Li, L.,Lv, P.,Hu, J.,Yang, J. Effect of breastfeeding on childhood BMI and obesity: the China Family Panel Studies. Medicine (Baltimore). 2014;93(10):e55. | Study design
1080 | Jochum, F.,Fuchs, A.,Cser, A.,Menzel, H.,Lombeck, I. Trace mineral status of full-term infants fed human milk, milk-based formula or partially hydrolysed whey protein formula. Analyst. 1995;120(3):905-9. | Included for systematic reviews not completed
1081 | Johansson, C.,Samuelsson, U.,Ludvigsson, J. A high weight gain early in life is associated with an increased risk of type 1 (insulin-dependent) diabetes mellitus. Diabetologia. 1994;37(1):91-4. | Included for systematic reviews not completed
1082 | Johnsen, D. C. Characteristics and backgrounds of children with “nursing caries”. Pediatr Dent. 1982;4(3):218-24. | Study design, Independent variable
1083 | Johnsen, D. C.,Gerstenmaier, J. H.,DiSantis, T. A.,Berkowitz, R. J. Susceptibility of nursing-caries children to future approximal molar decay. Pediatr Dent. 1986;8(3):168-70. | Study design
1084 | Johnsen, D. C.,Gerstenmaier, J. H.,Schwartz, E.,Michal, B. C.,Parrish, S. Background comparisons of pre-31/2-year-old children with nursing caries in four practice settings. Pediatr Dent. 1984;6(1):50-4. | Study design
1085 | Johnson, C. A.,Lieberman, B.,Hassanein, R. E. The relationship of breast feeding to third-day bilirubin levels. J Fam Pract. 1985;20(2):147-52. | Study design, Independent variable
1086 | Johnson, C. C.,Ownby, D. R.,Alford, S. H.,Havstad, S. L.,Williams, L. K.,Zoratti, E. M.,Peterson, E. L.,Joseph, C. L. Antibiotic exposure in early infancy and risk for childhood atopy. J Allergy Clin Immunol. 2005;115(6):1218-24. | Dependent variable
1087 | Johnson, D. L.,Swank, P. R.,Howie, V. M.,Baldwin, C. D.,Owen, M. Breast feeding and children’s intelligence. Psychol Rep. 1996;79(3 Pt 2):1179-85. | Included for systematic reviews not completed
1088 | Johnson, L.,van Jaarsveld, C. H.,Llewellyn, C. H.,Cole, T. J.,Wardle, J. Associations between infant feeding and the size, tempo and velocity of infant weight gain: SITAR analysis of the Gemini twin birth cohort. Int J Obes (Lond). 2014;38(7):980-7. | Included for systematic reviews not completed
1089 | Johnston, B. D.,Huebner, C. E.,Anderson, M. L.,Tyll, L. T.,Thompson, R. S. Healthy steps in an integrated delivery system: child and parent outcomes at 30 months. Arch Pediatr Adolesc Med. 2006;160(8):793-800. | Included for systematic reviews not completed
1090 | Johnston, P. K. Getting enough to grow on. Am J Nurs. 1984;84(3):336-9. | Study design, Independent variable, Dependent variable
1091 | Jonas, W.,Atkinson, L.,Steiner, M.,Meaney, M. J.,Wazana, A.,Fleming, A. S. Breastfeeding and maternal sensitivity predict early infant temperament. Acta Paediatr. 2015;104(7):678-86. | Included for systematic reviews not completed
1092 | Jones EG,Matheny RJ. Relationship between infant feeding and exclusion rate from child care because of illness. J Am Diet Assoc. 1993;93:809-11. | Study design, Dependent variable
1093 | Jones, A. INTERGENERATIONAL EDUCATIONAL ATTAINMENT, FAMILY CHARACTERISTICS AND CHILD OBESITY. J Biosoc Sci. 2015:1-20. | Study design
1094 | Jones, D. Infant feeding. Breast-feeding practices. Nurs Times. 1987;83(3):56-7. | Dependent variable
1095 | Jones, F.,Green, M. The B.C. Baby-Friendly Initiative. Nurs BC. 1996;28(5):7-8. | Study design
1096 | Jones, G.,Hynes, K. L.,Dwyer, T. The association between breastfeeding, maternal smoking in utero, and birth weight with bone mass and fractures in adolescents: a 16-year longitudinal study. Osteoporos Int. 2013;24(5):1605-11. | Included for systematic reviews not completed
1097 | Jones, G.,Riley, M.,Dwyer, T. Breastfeeding in early life and bone mass in prepubertal children: a longitudinal study. Osteoporos Int. 2000;11(2):146-52. | Included for systematic reviews not completed
1098 | Jones, I. E.,Williams, S. M.,Goulding, A. Associations of birth weight and length, childhood size, and smoking with bone fractures during growth: evidence from a birth cohort study. Am J Epidemiol. 2004;159(4):343-50. | Included for systematic reviews not completed
1099 | Jones, M. E.,Swerdlow, A. J.,Gill, L. E.,Goldacre, M. J. Pre-natal and early life risk factors for childhood onset diabetes mellitus: a record linkage study. Int J Epidemiol. 1998;27(3):444-9. | Independent variable
1100 | Jones, N. A.,McFall, B. A.,Diego, M. A. Patterns of brain electrical activity in infants of depressed mothers who breastfeed and bottle feed: the mediating role of infant temperament. Biol Psychol. 2004;67(1-2):103-24. | Group size
1101 | Jones, S. M.,Steele, R. W. Recurrent group B streptococcal bacteremia. Clin Pediatr (Phila). 2012;51(9):884-7. | Study design
1102 | Jones, T. F.,Ingram, L. A.,Fullerton, K. E.,Marcus, R.,Anderson, B. J.,McCarthy, P. V.,Vugia, D.,Shiferaw, B.,Haubert, N.,Wedel, S.,Angulo, F. J. A case-control study of the epidemiology of sporadic Salmonella infection in infants. Pediatrics. 2006;118(6):2380-7. | Independent variable
1103 | Jonsdottir, O. H.,Kleinman, R. E.,Wells, J. C.,Fewtrell, M. S.,Hibberd, P. L.,Gunnlaugsson, G.,Thorsdottir, I. Exclusive breastfeeding for 4 versus 6 months and growth in early childhood. Acta Paediatr. 2014;103(1):105-11. | Independent variable
1104 | Jonsdottir, O. H.,Thorsdottir, I.,Gunnlaugsson, G.,Fewtrell, M. S.,Hibberd, P. L.,Kleinman, R. E. Exclusive breastfeeding and developmental and behavioral status in early childhood. Nutrients. 2013;5(11):4414-28. | Independent variable
1105 | Jonsdottir, O. H.,Thorsdottir, I.,Hibberd, P. L.,Fewtrell, M. S.,Wells, J. C.,Palsson, G. I.,Lucas, A.,Gunnlaugsson, G.,Kleinman, R. E. Timing of the introduction of complementary foods in infancy: a randomized controlled trial. Pediatrics. 2012;130(6):1038-45. | Independent variable
1106 | Jonville-Béra, A. P.,Autret-Leca, E.,Barbeillon, F.,Paris-Llado, J. Sudden unexpected death in infants under 3 months of age and vaccination status - A case-control study. British Journal of Clinical Pharmacology. 2001;51(3):271-276. | Included for systematic reviews not completed
1107 | Jonville-Bera, A. P.,Autret-Leca, E.,Barbeillon, F.,Paris-Llado, J. Sudden unexpected death in infants under 3 months of age and vaccination status- -a case-control study. Br J Clin Pharmacol. 2001;51(3):271-6. | Included for systematic reviews not completed
1108 | Jooste, P. L.,Rossouw, L. J.,Steenkamp, H. J.,Rossouw, J. E.,Swanepoel, A. S.,Charlton, D. O. Effect of breast feeding on the plasma cholesterol and growth of infants. J Pediatr Gastroenterol Nutr. 1991;13(2):139-42. | Country
1109 | Jovanovic, D.,Ilic, N.,Miljkovic-Selimovic, B.,Djokic, D.,Relic, T.,Tambur, Z.,Doder, R.,Kostic, G. Campylobacter jejuni infection and IgE sensitization in up to 2-year-old infants. Vojnosanit Pregl. 2015;72(2):140-7. | Study design
1110 | Joventino, Emanuella Silva,Gomes Coutinho, Robson,de Castro Bezerra, Karine,de Almeida, Paulo CÃ©sar,Oliveira Batista OriÃ¡, MÃ´nica,Barbosa Ximenes, Lorena. Self-effectiveness in preventing diarrhea and child care: a transversal study. Online Brazilian Journal of Nursing. 2013;12(2):1-1 1p. | Study design
1111 | Juambeltz, J. C.,Kula, K.,Perman, J. Nursing caries and lactose intolerance. ASDC J Dent Child. 1993;60(4):377-84. | Study design, Independent variable
1112 | Juez, G.,Diaz, S.,Casado, M. E.,Duran, E.,Salvatierra, A. M.,Peralta, O.,Croxatto, H. B. Growth pattern of selected urban Chilean infants during exclusive breast-feeding. Am J Clin Nutr. 1983;38(3):462-8. | Independent variable
1113 | Juliusson, P. B.,Roelants, M.,Hoppenbrouwers, K.,Hauspie, R.,Bjerknes, R. Growth of Belgian and Norwegian children compared to the WHO growth standards: prevalence below −2 and above +2 SD and the effect of breastfeeding. Arch Dis Child. 2011;96(10):916-21. | Study design
1114 | Julvez, J.,Guxens, M.,Carsin, A. E.,Forns, J.,Mendez, M.,Turner, M. C.,Sunyer, J. A cohort study on full breastfeeding and child neuropsychological development: the role of maternal social, psychological, and nutritional factors. Dev Med Child Neurol. 2014;56(2):148-56. | Included for systematic reviews not completed
1115 | Julvez, J.,Ribas-Fito, N.,Forns, M.,Garcia-Esteban, R.,Torrent, M.,Sunyer, J. Attention behaviour and hyperactivity at age 4 and duration of breast-feeding. Acta Paediatr. 2007;96(6):842-7. | Included for systematic reviews not completed
1116 | Jung, E.,Czajka-Narins, D. Comparison of growth of black and white infants during their first two years of life. J Natl Med Assoc. 1986;78(12):1157-60. | Study design, Independent variable
1117 | Jung, E.,Czajka-Narins, D. M. Birth weight doubling and tripling times: an updated look at the effects of birth weight, sex, race and type of feeding. Am J Clin Nutr. 1985;42(2):182-9. | Independent variable
1118 | Just, J.,Belfar, S.,Wanin, S.,Pribil, C.,Grimfeld, A.,Duru, G. Impact of innate and environmental factors on wheezing persistence during childhood. J Asthma. 2010;47(4):412-6. | Health status
1119 | Juto, P.,Moller, C.,Engberg, S.,Bjorksten, B. Influence of type of feeding on lymphocyte function and development of infantile allergy. Clin Allergy. 1982;12(4):409-16. | Group size
1120 | Juvonen, P.,Mansson, M.,Andersson, C.,Jakobsson, I. Allergy development and macromolecular absorption in infants with different feeding regimens during the first three days of life. A three-year prospective follow-up. Acta Paediatr. 1996;85(9):1047-52. | Independent variable
1121 | Jwa, S. C.,Fujiwara, T.,Kondo, N. Latent protective effects of breastfeeding on late childhood overweight and obesity: a nationwide prospective study. Obesity (Silver Spring). 2014;22(6):1527-37. | Included for systematic reviews not completed
1122 | Kaatsch, P.,Kaletsch, U.,Krummenauer, F.,Meinert, R.,Miesner, A.,Haaf, G.,Michaelis, J. Case control study on childhood leukemia in Lower Saxony, Germany. Basic considerations, methodology, and summary of results. Klin Padiatr. 1996;208(4):179-85. | Study design, Independent variable
1123 | Kadziela-Olech, H.,Piotrowska-Jastrzebska, J. The duration of breastfeeding and attention deficit hyperactivity disorder. Rocz Akad Med Bialymst. 2005;50:302-6. | Included for systematic reviews not completed
1124 | Kafouri, S.,Kramer, M.,Leonard, G.,Perron, M.,Pike, B.,Richer, L.,Toro, R.,Veillette, S.,Pausova, Z.,Paus, T. Breastfeeding and brain structure in adolescence. Int J Epidemiol. 2013;42(1):150-9. | Study design
1125 | Kajosaari, M. Atopy prevention in childhood: the role of diet. Prospective 5-year follow-up of high-risk infants with six months exclusive breastfeeding and solid food elimination. Pediatr Allergy Immunol. 1994;5(6 Suppl):26-8. | Independent variable
1126 | Kajosaari, M. Atopy prophylaxis in high-risk infants. Prospective 5-year follow-up study of children with six months exclusive breastfeeding and solid food elimination. Adv Exp Med Biol. 1991;310:453-8. | Peer review
1127 | Kajosaari, M.,Saarinen, U. M. Prophylaxis of atopic disease by six months’ total solid food elimination. Evaluation of 135 exclusively breast-fed infants of atopic families. Acta Paediatr Scand. 1983;72(3):411-4. | Independent variable
1128 | Kale, A.,Deardorff, J.,Lahiff, M.,Laurent, C.,Greenspan, L. C.,Hiatt, R. A.,Windham, G.,Galvez, M. P.,Biro, F. M.,Pinney, S. M.,Teitelbaum, S. L.,Wolff, M. S.,Barlow, J.,Mirabedi, A.,Lasater, M.,Kushi, L. H. Breastfeeding versus formula-feeding and girls’ pubertal development. Matern Child Health J. 2015;19(3):519-27. | Study design, Dependent variable
1129 | Kalies, H.,Heinrich, J.,Borte, N.,Schaaf, B.,von Berg, A.,von Kries, R.,Wichmann, H. E.,Bolte, G. The effect of breastfeeding on weight gain in infants: results of a birth cohort study. Eur J Med Res. 2005;10(1):36-42. | Independent variable
1130 | Kallio, M. J.,Salmenpera, L.,Siimes, M. A.,Perheentupa, J.,Miettinen, T. A. Tracking of serum cholesterol and lipoprotein levels from the first year of life. Pediatrics. 1993;91(5):949-54. | Independent variable
1131 | Kallio, M. J.,Salmenpera, L.,Siimes, M. A.,Perheentupa, J.,Miettinen, T. A.. Exclusive breast-feeding and weaning: effect on serum cholesterol and lipoprotein concentrations in infants during the first year of life. Pediatrics. 1992;89(4 Pt 1):663-6. | Dependent variable
1132 | Kalliomaki, M.,Isolauri, E. Breastfeeding and atopic sensitisation. Adv Exp Med Biol. 2000;478:389-90. | Study design
1133 | Kalliomäki, M.,Salminen, S.,Arvilommi, H. Prenatal and postnatal administration of Lactobacillus GG reduced the occurence of atopic disease in offspring. Evidence-Based Medicine. 2001;6(6):178. | Study design
1134 | Kamer, B.,Raczynska, J.,Kaczmarek, J.,Lukamowicz, J.,Pasowska, R.,Puchala, B. Genetic and environmental conditions involved in assessment of the immunological state in children with atopic dermatitis. Rocz Akad Med Bialymst. 1995;40(3):439-47. | Study design, Health status
1135 | Kanazawa, S. Breastfeeding is positively associated with child intelligence even net of parental IQ. Dev Psychol. 2015;51(12):1683-9. | Included for systematic reviews not completed
1136 | Kaplan, B. A.,Mascie-Taylor, C. G. Biosocial factors in the epidemiology of childhood asthma in a British national sample. J Epidemiol Community Health. 1985;39(2):152-6. | Independent variable
1137 | Karaguzel, G.,Ozer, S.,Akcurin, S.,Turkkahraman, D.,Bircan, I. Type 1 diabetes-related epidemiological, clinical and laboratory findings. An evaluation with special regard to autoimmunity in children. Saudi Med J. 2007;28(4):584-9. | Health status
1138 | Karakoç, G. B.,Altintaş, D. U.,Yilmaz, M.,Kendirli, S. G. Prick Skin Test Results in Children Less Than Three Years-Old. Annals of Medical Sciences. 2003;12(3):85-88. | Health status
1139 | Karaolis-Danckert, N.,Buyken, A. E.,Kulig, M.,Kroke, A.,Forster, J.,Kamin, W.,Schuster, A.,Hornberg, C.,Keil, T.,Bergmann, R. L.,Wahn, U.,Lau, S. How pre- and postnatal risk factors modify the effect of rapid weight gain in infancy and early childhood on subsequent fat mass development: results from the Multicenter Allergy Study 90. Am J Clin Nutr. 2008;87(5):1356-64. | Included for systematic reviews not completed
1140 | Karaolis-Danckert, N.,Buyken, A. E.,Sonntag, A.,Kroke, A. Birth and early life influences on the timing of puberty onset: results from the DONALD (DOrtmund Nutritional and Anthropometric Longitudinally Designed) Study. Am J Clin Nutr. 2009;90(6):1559-65. | Dependent variable
1141 | Karaolis-Danckert, N.,Gunther, A. L.,Kroke, A.,Hornberg, C.,Buyken, A. E. How early dietary factors modify the effect of rapid weight gain in infancy on subsequent body-composition development in term children whose birth weight was appropriate for gestational age. Am J Clin Nutr. 2007;86(6):1700-8. | Independent variable
1142 | Karino, S.,Okuda, T.,Uehara, Y.,Toyo-oka, T. Breastfeeding and prevalence of allergic diseases in Japanese university students. Ann Allergy Asthma Immunol. 2008;101(2):153-9. | Study design
1143 | Karjalainen, S.,Ronning, O.,Lapinleimu, H.,Simell, O. Association between early weaning, non-nutritive sucking habits and occlusal anomalies in 3-year-old Finnish children. Int J Paediatr Dent. 1999;9(3):169-73. | Included for systematic reviews not completed
1144 | Kaseb, F.,Kimiagar, M.,Ghafarpoor, M.,Valaii, N. Effect of traditional food supplementation during pregnancy on maternal weight gain and birthweight. Int J Vitam Nutr Res. 2002;72(6):389-93. | Group size
1145 | Kasla, R. R.,Bavdekar, S. B.,Joshi, S. Y.,Hathi, G. S. Exclusive breastfeeding: protective efficacy. Indian J Pediatr. 1995;62(4):449-53. | Country
1146 | Kass, R. B.,Meumann, F. Hospitalisation for childhood diarrhoea in Central Australia. Aust Clin Rev. 1985;5(19):178-83. | Study design, Health status
1147 | Kaste, L. M.,Marianos, D.,Chang, R.,Phipps, K. R. The assessment of nursing caries and its relationship to high caries in the permanent dentition. 1992. J Indiana Dent Assoc. 2010;89(2):20-4. | Independent variable
1148 | Kato, T.,Yorifuji, T.,Yamakawa, M.,Inoue, S.,Saito, K.,Doi, H.,Kawachi, I. Association of breast feeding with early childhood dental caries: Japanese population-based study. BMJ Open. 2015;5(3):e006982. | Included for systematic reviews not completed
1149 | Katoku, Y.,Yamada, M.,Yonekubo, A.,Kuwata, T.,Kobayashi, A.,Sawa, A. Effect of the cholesterol content of a formula on the lipid compositions of plasma lipoproteins and red blood cell membranes in early infancy. Am J Clin Nutr. 1996;64(6):871-7. | Group size
1150 | Kaufman, H. S.,Frick, O. L. Prevention of asthma. Clin Allergy. 1981;11(6):549-53. | Independent variable
1151 | Kaur, N.,Deol, R.,Yadav, A. Correlation of feeding practices and health profile of children. Nurs J India. 2014;105(3):128-30. | Country
1152 | Kawai, T.,Goto, A.,Watanabe, E.,Nagasawa, M.,Yasumura, S. Lower respiratory tract infections and gastrointestinal infections among mature babies in Japan. Pediatr Int. 2011;53(4):431-45. | Study design
1153 | Kazemi, A.,Tabatabaie, F.,Agha-Ghazvini, M. R.,Kelishadi, R. The role of rotavirus in acute pediatric diarrhea in Isfahan, Iran. Pakistan Journal of Medical Sciences. 2006;22(3):282-285. | Study design
1154 | Keim, S. A.,Daniels, J. L.,Siega-Riz, A. M.,Herring, A. H.,Dole, N.,Scheidt, P. C. Breastfeeding and long-chain polyunsaturated fatty acid intake in the first 4 post-natal months and infant cognitive development: an observational study. Matern Child Nutr. 2012;8(4):471-82. | Included for systematic reviews not completed
1155 | Kellberger, J.,Dressel, H.,Vogelberg, C.,Leupold, W.,Windstetter, D.,Weinmayr, G.,Genuneit, J.,Heumann, C.,Nowak, D.,von Mutius, E.,Radon, K. Prediction of the incidence and persistence of allergic rhinitis in adolescence: a prospective cohort study. J Allergy Clin Immunol. 2012;129(2):397-402, 402 e1-3. | Independent variable
1156 | Keller, K. M.,Burgin-Wolff, A.,Lippold, R.,Wirth, S.,Lentze, M. J. The diagnostic significance of IgG cow’s milk protein antibodies re-evaluated. Eur J Pediatr. 1996;155(4):331-7. | Dependent variable
1157 | Keller, K. M.,Burgin-Wolff, A.,Menger, H.,Lippold, R.,Wirth, S.,Baumann, W. IgG, IgA, and IgE antibodies to cow milk proteins in an allergy prevention study. Adv Exp Med Biol. 1991;310:467-73. | Independent variable, Dependent variable
1158 | Kemeny, D. M.,Price, J. F.,Richardson, V.,Richards, D.,Lessof, M. H. The IgE and IgG subclass antibody response to foods in babies during the first year of life and their relationship to feeding regimen and the development of food allergy. J Allergy Clin Immunol. 1991;87(5):920-9. | Dependent variable
1159 | Kennedy, K.,Fewtrell, M. S.,Morley, R.,Abbott, R.,Quinlan, P. T.,Wells, J. C.,Bindels, J. G.,Lucas, A. Double-blind, randomized trial of a synthetic triacylglycerol in formula-fed term infants: effects on stool biochemistry, stool characteristics, and bone mineralization. Am J Clin Nutr. 1999;70(5):920-7. | Included for systematic reviews not completed
1160 | Kero, P.,Piekkala, P. Factors affecting the occurrence of acute otitis media during the first year of life. Acta Paediatr Scand. 1987;76(4):618-23. | Included for systematic reviews not completed
1161 | Kerr, A. A. Lower respiratory tract illness in Polynesian infants. N Z Med J. 1981;93(684):333-5. | Study design, Dependent variable
1162 | Keusch, G. T. Homing in on interventions in the malnutrition-infection complex. Am J Clin Nutr. 1980;33(4):727-9. | Study design
1163 | Khadivzadeh, T.,Parsai, S. Effect of exclusive breastfeeding and complementary feeding on infant growth and morbidity. East Mediterr Health J. 2004;10(3):289-94. | Independent variable
1164 | Khalili, H.,Ananthakrishnan, A. N.,Higuchi, L. M.,Richter, J. M.,Fuchs, C. S.,Chan, A. T. Early life factors and risk of inflammatory bowel disease in adulthood. Inflamm Bowel Dis. 2013;19(3):542-7. | Independent variable
1165 | Khan, F.,Green, F. C.,Forsyth, J. S.,Greene, S. A.,Newton, D. J.,Belch, J. J. The beneficial effects of breastfeeding on microvascular function in 11- to 14-year-old children. Vasc Med. 2009;14(2):137-42. | Independent variable
1166 | Khanjanasthiti, P.,Nanna, P.,Sawongtrakul, S. Breast feeding in early neonatal period. J Med Assoc Thai. 1986;69 Suppl 2:100-6. | Dependent variable
1167 | Khanolkar, A. R.,Sovio, U.,Bartlett, J. W.,Wallby, T.,Koupil, I. Socioeconomic and early-life factors and risk of being overweight or obese in children of Swedish- and foreign-born parents. Pediatr Res. 2013;74(3):356-63. | Independent variable
1168 | Khedr, E. M.,Farghaly, W. M.,Amry Sel, D.,Osman, A. A. Neural maturation of breastfed and formula-fed infants. Acta Paediatr. 2004;93(6):734-8. | Country
1169 | Kholdi, N.,Zayeri, F.,Bagheban, A. A.,Khodakarim, S.,Ramezankhani, A. A study of growth failure and its related factors in children from 0 to 2 years in Tehran, Iran. Turk J Pediatr. 2012;54(1):38-44. | Included for systematic reviews not completed
1170 | Kiechl-Kohlendorfer, U.,Horak, E.,Mueller, W.,Strobl, R.,Haberland, C.,Fink, F. M.,Schwaiger, M.,Gutenberger, K. H.,Reich, H.,Meraner, D.,Kiechl, S. Neonatal characteristics and risk of atopic asthma in schoolchildren: results from a large prospective birth-cohort study. Acta Paediatr. 2007;96(11):1606-10. | Independent variable
1171 | Kiechl-Kohlendorfer, U.,Peglow, U. P.,Kiechl, S.,Oberaigner, W.,Sperl, W. Epidemiology of sudden infant death syndrome (SIDS) in the Tyrol before and after an intervention campaign. Wien Klin Wochenschr. 2001;113(1-2):27-32. | Study design, Independent variable
1172 | Kieviet, N.,Hoppenbrouwers, C.,Dolman, K. M.,Berkhof, J.,Wennink, H.,Honig, A. Risk factors for poor neonatal adaptation after exposure to antidepressants in utero. Acta Paediatr. 2015;104(4):384-91. | Dependent variable
1173 | Kim, C. S.,Jung, H. W.,Yoo, K. Y. Prevalence and risk factors of chronic otitis media in Korea: results of a nation-wide survey. Acta Otolaryngol. 1993;113(3):369-75. | Study design
1174 | Kim, H. S.,Kim, Y. H.,Kim, M. J.,Lee, H. S.,Han, Y. K.,Kim, K. W.,Sohn, M. H.,Kim, K. E. Effect of breastfeeding on lung function in asthmatic children. Allergy Asthma Proc. 2015;36(2):116-22. | Study design, Health status
1175 | Kim, I.,Pollitt, E. Differences in the pattern of weight growth of nutritionally at-risk and well-nourished infants. Am J Clin Nutr. 1987;46(1):31-5. | Independent variable
1176 | Kim, S. K.,Cheong, W. S.,Jun, Y. H.,Choi, J. W.,Son, B. K. Red blood cell indices and iron status according to feeding practices in infants and young children. Acta Paediatr. 1996;85(2):139-44. | Study design, Health status
1177 | Kimpimaki, T.,Erkkola, M.,Korhonen, S.,Kupila, A.,Virtanen, S. M.,Ilonen, J.,Simell, O.,Knip, M. Short-term exclusive breastfeeding predisposes young children with increased genetic risk of Type I diabetes to progressive beta-cell autoimmunity. Diabetologia. 2001;44(1):63-9. | Dependent variable
1178 | King, D. E. Statistics. Adult intelligence and breastfeeding. International Journal of Childbirth Education. 2002;17(4):23-23 1p. | Peer review
1179 | Kiris, M.,Muderris, T.,Kara, T.,Bercin, S.,Cankaya, H.,Sevil, E. Prevalence and risk factors of otitis media with effusion in school children in Eastern Anatolia. International Journal of Pediatric Otorhinolaryngology. 2012;76(7):1030-1035. | Study design
1180 | Kitsantas, P.,Gaffney, K. F. Risk profiles for overweight/obesity among preschoolers. Early Hum Dev. 2010;86(9):563-8. | Included for systematic reviews not completed
1181 | Kjellman, N. I. Epidemiology and prevention of allergy. Allergy. 1988;43 Suppl 8:39-40. | Study design
1182 | Klag, E. A.,McNamara, K.,Geraghty, S. R.,Keim, S. A. Associations Between Breast Milk Feeding, Introduction of Solid Foods, and Weight Gain in the First 12 Months of Life. Clin Pediatr (Phila). 2015;54(11):1059-67. | Study design
1183 | Klein, I.,Reif, S.,Farbstein, H.,Halak, A.,Gilat, T. Preillness non dietary factors and habits in inflammatory bowel disease. Ital J Gastroenterol Hepatol. 1998;30(3):247-51. | Independent variable
1184 | Klein, J. O. Prevention of recurrent acute otitis media. Seminars in Pediatric Infectious Diseases. 1997;8(2):101-104. | Study design
1185 | Klenovics, K. S.,Boor, P.,Somoza, V.,Celec, P.,Fogliano, V.,Sebekova, K. Advanced glycation end products in infant formulas do not contribute to insulin resistance associated with their consumption. PLoS One. 2013;8(1):e53056. | Study design
1186 | Klonoff-Cohen, H. S.,Edelstein, S. L.,Lefkowitz, E. S.,Srinivasan, I. P.,Kaegi, D.,Chang, J. C.,Wiley, K. J. The effect of passive smoking and tobacco exposure through breast milk on sudden infant death syndrome. JAMA. 1995;273(10):795-8. | Included for systematic reviews not completed
1187 | Knight, S. M.,Toodayan, W.,Caique, W. C.,Kyi, W.,Barnes, A.,Desmarchelier, P. Risk factors for the transmission of diarrhoea in children: a case-control study in rural Malaysia. Int J Epidemiol. 1992;21(4):812-8. | Health status
1188 | Knip, M. Cow’s milk and the new trials for prevention of type 1 diabetes. J Endocrinol Invest. 2003;26(3):265-7. | Study design
1189 | Knishkowy, B.,Palti, H.,Adler, B.,Tepper, D. Effect of otitis media on development: a community-based study. Early Hum Dev. 1991;26(2):101-11. | Included for systematic reviews not completed
1190 | Koch, A.,Molbak, K.,Homoe, P.,Sorensen, P.,Hjuler, T.,Olesen, M. E.,Pejl, J.,Pedersen, F. K.,Olsen, O. R.,Melbye, M. Risk factors for acute respiratory tract infections in young Greenlandic children. Am J Epidemiol. 2003;158(4):374-84. | Included for systematic reviews not completed
1191 | Kocturk, T. Infant feeding pattern in three districts of Istanbul. J Trop Pediatr. 1988;34(4):193-7. | Study design, Dependent variable
1192 | Koehoorn, M.,Karr, C. J.,Demers, P. A.,Lencar, C.,Tamburic, L.,Brauer, M. Descriptive epidemiological features of bronchiolitis in a population-based cohort. Pediatrics. 2008;122(6):1196-203. | Included for systematic reviews not completed
1193 | Koenig, H. F. Breastfeeding education for healthier babies. Baby-Friendly designation improves infant, mother and community health. Healthc Exec. 2014;29(4):46, 48-9. | Study design
1194 | Koh, T. H. Breast feeding among the Chinese in four countries. J Trop Pediatr. 1981;27(2):88-91. | Study design, Dependent variable
1195 | Kohler, L.,Meeuwisse, G.,Mortensson, W. Food intake and growth of infants between six and twenty-six weeks of age on breast milk, cow’s milk formula, or soy formula. Acta Paediatr Scand. 1984;73(1):40-8. | Group size
1196 | Kohn, G.,Sawatzki, G.,van Biervliet, J. P.,Rosseneu, M. Diet and the essential fatty acid status of term infants. Acta Paediatr Suppl. 1994;402:69-74. | Included for systematic reviews not completed
1197 | Kolacek, S.,Kapetanovic, T.,Luzar, V. Early determinants of cardiovascular risk factors in adults. B. Blood pressure. Acta Paediatr. 1993;82(4):377-82. | Group size
1198 | Kolacek, S.,Kapetanovic, T.,Zimolo, A.,Luzar, V. Early determinants of cardiovascular risk factors in adults. A. Plasma lipids. Acta Paediatr. 1993;82(8):699-704. | Group size
1199 | Koletzko S. 2.5 Allergy Prevention through Early Nutrition. World Rev Nutr Diet. 2015;113:113-7. | Peer review
1200 | Koletzko, B. 2.2 Formula feeding. World Rev Nutr Diet. 2015;113:97-103. | Study design
1201 | Koletzko, B.,Beyer, J.,Brands, B.,Demmelmair, H.,Grote, V.,Haile, G.,Gruszfeld, D.,Rzehak, P.,Socha, P.,Weber, M. Early influences of nutrition on postnatal growth. Nestle Nutr Inst Workshop Ser. 2013;71:11-27. | Study design
1202 | Koletzko, B.,Grote, V.,Schiess, S.,Verwied-Jorky, S.,Brands, B.,Demmelmair, H.,Kries, R. Prevention of pediatric obesity through baby nutrition. [German]. Monatsschrift fur Kinderheilkunde. 2010;158(6):553-63. | Language
1203 | Koletzko, B.,Schiess, S.,Brands, B.,Haile, G.,Demmelmair, H.,Kries, R.,Grote, V. [Infant feeding practice and later obesity risk. Indications for early metabolic programming]. Bundesgesundheitsblatt, Gesundheitsforschung, Gesundheitsschutz. 2010;53(7):666-73. | Language
1204 | Koletzko, B.,Toschke, A. M.,Vignerova, J.,Osancova, K.,Von Kries, R. Does breast feeding protect against later overweight and obesity?. Cesko-Slovenska Pediatrie. 2003;58(1):3-9. | Study design
1205 | Koletzko, B.,von Kries, R. Are there long term protective effects of breast feeding against later obesity?. Pediatria Wspolczesna. 2002;4(3):217-223. | Language
1206 | Koletzko, B.,Von Kries, R.,Closa, R.,Escribano, J.,Scaglioni, S.,Giovannini, M.,Beyer, J.,Demmelmair, H.,Gruszfeld, D.,Dobrzanska, A.,Sengier, A.,Langhendries, J. P.,Cachera, M. F. R.,Grote, V. Lower protein in infant formula is associated with lower weight up to age 2 y: A randomized clinical trial. American Journal of Clinical Nutrition. 2009;89(6):1836-1845. | Included for systematic reviews not completed
1207 | Koletzko, B.,von, K. R.,Closa, R.,Escribano, J.,Scaglioni, S.,Giovannini, M.,Beyer, J.,Demmelmair, H.,Anton, B.,Gruszfeld, D.,Dobrzanska, A.,Sengier, A.,Langhendries, J. P.,Rolland Cachera, M. F.,Grote, V. Can infant feeding choices modulate later obesity risk?. American journal of clinical nutrition. 2009;89(5):1502s-1508s. | Study design
1208 | Koloski, N. A.,Jones, M.,Weltman, M.,Kalantar, J.,Bone, C.,Gowryshankar, A.,Walker, M. M.,Talley, N. J. Identification of early environmental risk factors for irritable bowel syndrome and dyspepsia. Neurogastroenterol Motil. 2015;27(9):1317-25. | Dependent variable
1209 | Koopman, J. S.,Turkish, V. J.,Monto, A. S. Infant formulas and gastrointestinal illness. Am J Public Health. 1985;75(5):477-80. | Included for systematic reviews not completed
1210 | Kosse, F. The Nutritional and Social Environment-Related Effects of Breastfeeding on Intelligence. JAMA Pediatr. 2016;170(2):173-4. | Study design, Dependent variable
1211 | Koster, E. S.,Van der Ent, C. K.,Uiterwaal, C. S.,Verheij, T. J.,Raaijmakers, J. A.,Maitland-van der Zee, A. H. Asthma medication use in infancy: determinants related to prescription of drug therapy. Fam Pract. 2011;28(4):377-84. | Independent variable
1212 | Krabbendam, L.,Bakker, E.,Hornstra, G.,van Os, J. Relationship between DHA status at birth and child problem behaviour at 7 years of age. Prostaglandins Leukot Essent Fatty Acids. 2007;76(1):29-34. | Included for systematic reviews not completed
1213 | Kramer, M. S. Do breast-feeding and delayed introduction of solid foods protect against subsequent obesity?. J Pediatr. 1981;98(6):883-7. | Included for systematic reviews not completed
1214 | Kramer, M. S. Infant feeding, infection, and public health. Pediatrics. 1988;81(1):164-6. | Study design
1215 | Kramer, M. S.,Aboud, F.,Mironova, E.,Vanilovich, I.,Platt, R. W.,Matush, L.,Igumnov, S.,Fombonne, E.,Bogdanovich, N.,Ducruet, T.,Collet, J. P.,Chalmers, B.,Hodnett, E.,Davidovsky, S.,Skugarevsky, O.,Trofimovich, O.,Kozlova, L.,Shapiro, S. Breastfeeding and child cognitive development: new evidence from a large randomized trial. Arch Gen Psychiatry. 2008;65(5):578-84. | Included for systematic reviews not completed
1216 | Kramer, M. S.,Barr, R. G.,Leduc, D. G.,Boisjoly, C.,McVey-White, L.,Pless, I. B. Determinants of weight and adiposity in the first year of life. J Pediatr. 1985;106(1):10-4. | Included for systematic reviews not completed
1217 | Kramer, M. S.,Barr, R. G.,Pless, I. B. Determinants of weight and adiposity in early childhood. Canadian Journal of Public Health. 1986;77(SUPPL. 1):98-103. | Included for systematic reviews not completed
1218 | Kramer, M. S.,Fombonne, E.,Igumnov, S.,Vanilovich, I.,Matush, L.,Mironova, E.,Bogdanovich, N.,Tremblay, R. E.,Chalmers, B.,Zhang, X.,Platt, R. W. Effects of prolonged and exclusive breastfeeding on child behavior and maternal adjustment: evidence from a large, randomized trial. Pediatrics. 2008;121(3):e435-40. | Included for systematic reviews not completed
1219 | Kramer, M. S.,Fombonne, E.,Matush, L.,Bogdanovich, N.,Dahhou, M.,Platt, R. W. Long-term behavioural consequences of infant feeding: the limits of observational studies. Paediatr Perinat Epidemiol. 2011;25(6):500-6. | Included for systematic reviews not completed
1220 | Kramer, M. S.,Guo, T.,Platt, R. W.,Sevkovskaya, Z.,Dzikovich, I.,Collet, J. P.,Shapiro, S.,Chalmers, B.,Hodnett, E.,Vanilovich, I.,Mezen, I.,Ducruet, T.,Shishko, G.,Bogdanovich, N. Infant growth and health outcomes associated with 3 compared with 6 mo of exclusive breastfeeding. Am J Clin Nutr. 2003;78(2):291-5. | Included for systematic reviews not completed
1221 | Kramer, M. S.,Guo, T.,Platt, R. W.,Shapiro, S.,Collet, J. P.,Chalmers, B.,Hodnett, E.,Sevkovskaya, Z.,Dzikovich, I.,Vanilovich, I. Breastfeeding and infant growth: biology or bias?. Pediatrics. 2002;110(2 Pt 1):343-7. | Included for systematic reviews not completed
1222 | Kramer, M. S.,Guo, T.,Platt, R. W.,Vanilovich, I.,Sevkovskaya, Z.,Dzikovich, I.,Michaelsen, K. F.,Dewey, K. Feeding effects on growth during infancy. J Pediatr. 2004;145(5):600-5. | Independent variable
1223 | Kramer, M. S.,Martin, R. M.,Bogdanovich, N.,Vilchuk, K.,Dahhou, M.,Oken, E. Is restricted fetal growth associated with later adiposity? Observational analysis of a randomized trial. Am J Clin Nutr. 2014;100(1):176-81. | Included for systematic reviews not completed
1224 | Kramer, M. S.,Matush, L.,Aboud, F.,Vanilovich, I.,Bogdanovich, N.,Mironova, E. Long-term child health effects of breastfeeding in developed countries: new evidence from the PROBIT trial [abstract]. Journal of human lactation. 2007;23(1):90. | Study design
1225 | Kramer, M. S.,Matush, L.,Bogdanovich, N.,Dahhou, M.,Platt, R. W.,Mazer, B. The low prevalence of allergic disease in Eastern Europe: are risk factors consistent with the hygiene hypothesis?. Clin Exp Allergy. 2009;39(5):708-16. | Independent variable
1226 | Kramer, M. S.,Matush, L.,Vanilovich, I.,Platt, R. W.,Bogdanovich, N.,Sevkovskaya, Z.,Dzikovich, I.,Shishko, G.,Collet, J. P.,Martin, R. M.,Smith, G. D.,Gillman, M. W.,Chalmers, B.,Hodnett, E.,Shapiro, S. A randomized breast-feeding promotion intervention did not reduce child obesity in Belarus. J Nutr. 2009;139(2):417S-21S. | Study design
1227 | Kramer, M. S.,Moodie, E. E.,Dahhou, M.,Platt, R. W. Breastfeeding and infant size: evidence of reverse causality. Am J Epidemiol. 2011;173(9):978-83. | Independent variable
1228 | Kramer, M. S.,Moodie, E. E.,Platt, R. W. Infant feeding and growth: can we answer the causal question?. Epidemiology. 2012;23(6):790-4. | Study design
1229 | Kramer, M. S.,Moroz, B. Do breast-feeding and delayed introduction of solid foods protect against subsequent atopic eczema?. J Pediatr. 1981;98(4):546-50. | Study design
1230 | Kramer, M. S.,Vanilovich, I.,Matush, L.,Bogdanovich, N.,Zhang, X.,Shishko, G.,Muller-Bolla, M.,Platt, R. W. The effect of prolonged and exclusive breast-feeding on dental caries in early school-age children. New evidence from a large randomized trial. Caries Res. 2007;41(6):484-8. | Included for systematic reviews not completed
1231 | Kramer, M.,Matush, L.,Vanilovich, I.,Platt, R.,Mazer, B. Does breastfeeding help prevent asthma and allergy? Evidence from a randomized trial in Belarus. American journal of epidemiology. 2006;163(Suppl 11):S85. | Peer review
1232 | Kramer,M, S.,Matush,L,Vanilovich,I,Platt,R, W.,Bogdanovich,N,Sevkovskaya,Z,Dzikovich,I,Shishko,G,Collet,J, P.,Martin,R, M.,Davey, Smith,G,Gillman,M, W.,Chalmers,B,Hodnett,E,Shapiro,S,. Effects of prolonged and exclusive breastfeeding on child height, weight, adiposity, and blood pressure at age 6.5 y: evidence from a large randomized trial. Am J Clin Nutr. 2007;86(6):1717-21. | Duplicate
1233 | Kraus, J. F.,Greenland, S.,Bulterys, M. Risk factors for sudden infant death syndrome in the US Collaborative Perinatal Project. Int J Epidemiol. 1989;18(1):113-20. | Included for systematic reviews not completed
1234 | Kravetz, R. E. Infant nursing bottle. Am J Gastroenterol. 2003;98(7):1640. | Study design, Dependent variable
1235 | Krebs, N. F.,Hambidge, K. M.,Westcott, J. E.,Miller, L. V.,Sian, L.,Bell, M.,Grunwald, G. Exchangeable zinc pool size in infants is related to key variables of zinc homeostasis. J Nutr. 2003;133(5 Suppl 1):1498S-501S. | Study design
1236 | Krebs, N. F.,Reidinger, C. J.,Robertson, A. D.,Hambidge, K. M. Growth and intakes of energy and zinc in infants fed human milk. J Pediatr. 1994;124(1):32-9. | Independent variable
1237 | Krebs, N. F.,Reidinger, C.,Westcott, J.,Miller, L. V.,Fennessey, P. V.,Hambidge, K. M. Whole body zinc metabolism in full-term breasted and formula fed infants. Adv Exp Med Biol. 1994;352:223-6. | Study design
1238 | Krebs, N. F.,Westcott, J. E.,Culbertson, D. L.,Sian, L.,Miller, L. V.,Hambidge, K. M. Comparison of complementary feeding strategies to meet zinc requirements of older breastfed infants. Am J Clin Nutr. 2012;96(1):30-5. | Independent variable
1239 | Krenz-Niedbala, M.,Puch, E. A.,Koscinski, K. Season of birth and subsequent body size: the potential role of prenatal vitamin D. Am J Hum Biol. 2011;23(2):190-200. | Study design
1240 | Krishna, L. M. Breast feeding and development. Public Health. 1980;94(1):21-4. | Study design
1241 | Krous, H. F.,Chadwick, A. E.,Stanley, C. Delayed infant death following catastrophic deterioration during breast-feeding. J Paediatr Child Health. 2005;41(4):215-7. | Study design
1242 | Kucukcongar A,Oguz A,Pinarli FG,Karadeniz C,Okur A,Kaya Z,Celik B. Breastfeeding and Childhood Cancer: Is Breastfeeding Preventative to Childhood Cancer?. Pediatr Hematol Oncol. 2015;32:374-81. | Dependent variable
1243 | Küçükçongar, A.,Oʇuz, A.,Pinarli, F. G.,Karadeniz, C.,Okur, A.,Kaya, Z.,Çelik, B. Breastfeeding and Childhood Cancer: Is Breastfeeding Preventative to Childhood Cancer?. Pediatric Hematology and Oncology. 2015;32(6):374-381. | Dependent variable
1244 | Kucur, C.,Simsek, E.,Kuduban, O.,Ozbay, I. Prevalence of and risk factors for otitis media with effusion in primary school children: case control study in Erzurum, Turkey. Turk J Pediatr. 2015;57(3):230-5. | Study design, Dependent variable
1245 | Kuhn, T.,Kroke, A.,Remer, T.,Schonau, E.,Buyken, A. E. Is breastfeeding related to bone properties? A longitudinal analysis of associations between breastfeeding duration and pQCT parameters in children and adolescents. Matern Child Nutr. 2014;10(4):642-9. | Independent variable
1246 | Kuhnisch, J.,Mach, D.,Thiering, E.,Brockow, I.,Hoffmann, U.,Neumann, C.,Heinrich-Weltzien, R.,Bauer, C. P.,Berdel, D.,von Berg, A.,Koletzko, S.,Garcia-Godoy, F.,Hickel, R.,Heinrich, J. Respiratory diseases are associated with molar-incisor hypomineralizations. Swiss Dent J. 2014;124(3):286-93. | Included for systematic reviews not completed
1247 | Kuiper, S.,Muris, J. W.,Dompeling, E.,Kester, A. D.,Wesseling, G.,Knottnerus, J. A.,van Schayck, C. P. Interactive effect of family history and environmental factors on respiratory tract-related morbidity in infancy. J Allergy Clin Immunol. 2007;120(2):388-95. | Included for systematic reviews not completed
1248 | Kukkonen, A. K.,Savilahti, E. M.,Haahtela, T.,Savilahti, E.,Kuitunen, M. Ovalbumin-specific immunoglobulins A and G levels at age 2 years are associated with the occurrence of atopic disorders. Clin Exp Allergy. 2011;41(10):1414-21. | Independent variable
1249 | Kull, I.,Bohme, M.,Wahlgren, C. F.,Nordvall, L.,Pershagen, G.,Wickman, M. Breast-feeding reduces the risk for childhood eczema. J Allergy Clin Immunol. 2005;116(3):657-61. | Independent variable
1250 | Kull, I.,Melen, E.,Alm, J.,Hallberg, J.,Svartengren, M.,van Hage, M.,Pershagen, G.,Wickman, M.,Bergstrom, A. Breast-feeding in relation to asthma, lung function, and sensitization in young schoolchildren. J Allergy Clin Immunol. 2010;125(5):1013-9. | Independent variable
1251 | Kumar, A. Breast feeding versus bottle feeding. J Indian Med Assoc. 1985;83(10):365-6. | Study design
1252 | Kumar, V.,Sharma, S.,Khanna, P.,Vanaja, K. Breast vs bottle feeding-impact on growth in urban infants. Indian J Pediatr. 1981;48(392):271-5. | Country
1253 | Kumari, S.,Jain, P.,Arora, U.,Pruthi, R. K. Growth of breast fed infants. A longitudinal study. Indian Pediatr. 1982;19(12):963-8. | Country
1254 | Kumari, S.,Pruthi, P. K.,Mehra, R.,Sehgal, H. Breast feeding: physical growth during infancy. Indian J Pediatr. 1985;52(414):73-7. | Country
1255 | Kuperberg, K.,Evers, S. Feeding patterns and weight among First Nations children. Can J Diet Pract Res. 2006;67(2):79-84. | Independent variable
1256 | Kupers, L. K.,L’Abee, C.,Bocca, G.,Stolk, R. P.,Sauer, P. J.,Corpeleijn, E. Determinants of Weight Gain during the First Two Years of Life--The GECKO Drenthe Birth Cohort. PLoS One. 2015;10(7):e0133326. | Included for systematic reviews not completed
1257 | Kuriakose, J. R. Nutritional status and feeding practices of infants. Nurs J India. 2010;101(8):184-6. | Country
1258 | Kurugol, Z.,Coker, M.,Coker, C.,Egemen, A.,Ersoz, B. Comparison of growth, serum prealbumin, transferrin, IgG and amino acids of term infants fed breast mild or formula. Turk J Pediatr. 1997;39(2):195-202. | Group size
1259 | Kurugol, Z.,Geylani, S.,Karaca, Y.,Umay, F.,Erensoy, S.,Vardar, F.,Bak, M.,Yaprak, I.,Ozkinay, F.,Ozkinay, C. Rotavirus gastroenteritis among children under five years of age in Izmir, Turkey. Turk J Pediatr. 2003;45(4):290-4. | Independent variable, Health status
1260 | Kurugöl, Z.,Geylani, S.,Karaca, Y.,Umay, F.,Erensoy, S.,Vardar, F.,Bak, M.,Yaprak, I.,Özkinay, F.,Özkinay, C. Rotavirus gastroenteritis among children under five years of age in ˙Izmir, Turkey. Turkish Journal of Pediatrics. 2003;45(4):290-294. | Study design, Independent variable
1261 | Kurukulaaratchy, R. J.,Matthews, S.,Arshad, S. H. Relationship between childhood atopy and wheeze: what mediates wheezing in atopic phenotypes?. Ann Allergy Asthma Immunol. 2006;97(1):84-91. | Independent variable
1262 | Kurzewski, K.,Gardner, J. M. Breastfeeding patterns among six-week-old term infants at the University Hospital of the West Indies. West Indian Med J. 2005;54(1):28-33. | Study design
1263 | Kusunoki, T.,Morimoto, T.,Nishikomori, R.,Yasumi, T.,Heike, T.,Mukaida, K.,Fujii, T.,Nakahata, T. Breastfeeding and the prevalence of allergic diseases in schoolchildren: Does reverse causation matter?. Pediatric Allergy and Immunology. 2010;21(1 PART I):60-66. | Study design
1264 | Kuyucu, S.,Saraclar, Y.,Tuncer, A.,Sackesen, C.,Adalioglu, G.,Sumbuloglu, V.,Sekerel, B. E. Determinants of atopic sensitization in Turkish school children: effects of pre- and post-natal events and maternal atopy. Pediatr Allergy Immunol. 2004;15(1):62-71. | Study design
1265 | Kvaavik, E.,Tell, G. S.,Klepp, K. I. Surveys of Norwegian youth indicated that breast feeding reduced subsequent risk of obesity. J Clin Epidemiol. 2005;58(8):849-55. | Included for systematic reviews not completed
1266 | Kwok, M. K.,Leung, G. M.,Schooling, C. M. Breast feeding and early adolescent behaviour, self-esteem and depression: Hong Kong’s ‘Children of 1997’ birth cohort. Arch Dis Child. 2013;98(11):887-94. | Included for systematic reviews not completed
1267 | Kwok, M. K.,Schooling, C. M.,Lam, T. H.,Leung, G. M. Does breastfeeding protect against childhood overweight? Hong Kong’s ‘Children of 1997’ birth cohort. Int J Epidemiol. 2010;39(1):297-305. | Included for systematic reviews not completed
1268 | Labayen, I.,Ortega, F. B.,Ruiz, J. R.,Rodriguez, G.,Jiménez-Pavón, D.,España-Romero, V.,Widhalm, K.,Gottrand, F.,Moreno, L. A. Breastfeeding attenuates the effect of low birthweight on abdominal adiposity in adolescents: The HELENA study. Maternal and Child Nutrition. 2015;11(4):1036-1040. | Study design
1269 | Labayen, I.,Ruiz, J. R.,Ortega, F. B.,Loit, H. M.,Harro, J.,Villa, I.,Veidebaum, T.,Sjostrom, M. Exclusive breastfeeding duration and cardiorespiratory fitness in children and adolescents. Am J Clin Nutr. 2012;95(2):498-505. | Study design
1270 | Labbok, M. H. Consequences of breast-feeding for mother and child. J Biosoc Sci Suppl. 1985;9:43-54. | Study design
1271 | Ladd GA. Merlin’s molars. Cal. 1986;49:14-5, 31. | Study design
1272 | Laditan, A. A. Bilateral genu vara in childhood. Cent Afr J Med. 1983;29(11):219-23. | Dependent variable, Country
1273 | Ladomenou, F.,Kafatos, A.,Galanakis, E. Environmental tobacco smoke exposure as a risk factor for infections in infancy. Acta Paediatr. 2009;98(7):1137-41. | Independent variable
1274 | Ladomenou, F.,Kafatos, A.,Tselentis, Y.,Galanakis, E. Predisposing factors for acute otitis media in infancy. J Infect. 2010;61(1):49-53. | Included for systematic reviews not completed
1275 | Ladomenou, F.,Moschandreas, J.,Kafatos, A.,Tselentis, Y.,Galanakis, E. Protective effect of exclusive breastfeeding against infections during infancy: a prospective study. Arch Dis Child. 2010;95(12):1004-8. | Included for systematic reviews not completed
1276 | Lakhani SA,Chaudhri T,Jansen AA. Human milk and milk formulas for infant feeding. East Afr Med J. 1983;60:181-5. | Study design
1277 | Lakshman, R.,Whittle, F.,Hardeman, W.,Suhrcke, M.,Wilson, E.,Griffin, S.,Ong, K. K. Effectiveness of a behavioural intervention to prevent excessive weight gain during infancy (The Baby Milk Trial): study protocol for a randomised controlled trial. Trials. 2015;16(1):442. | Study design, Independent variable
1278 | Lamb, M. M.,Dabelea, D.,Yin, X.,Ogden, L. G.,Klingensmith, G. J.,Rewers, M.,Norris, J. M. Early-life predictors of higher body mass index in healthy children. Ann Nutr Metab. 2010;56(1):16-22. | Included for systematic reviews not completed
1279 | Lamb, M. M.,Simpson, M. D.,Seifert, J.,Scott, F. W.,Rewers, M.,Norris, J. M. The association between IgG4 antibodies to dietary factors, islet autoimmunity and type 1 diabetes: the Diabetes Autoimmunity Study in the Young. PLoS One. 2013;8(2):e57936. | Dependent variable
1280 | Lamichhane, A. P.,Crandell, J. L.,Jaacks, L. M.,Couch, S. C.,Lawrence, J. M.,Mayer-Davis, E. J. Longitudinal associations of nutritional factors with glycated hemoglobin in youth with type 1 diabetes: the SEARCH Nutrition Ancillary Study. Am J Clin Nutr. 2015;101(6):1278-85. | Dependent variable, Health status
1281 | Lanari, M.,Adorni, F.,Silvestri, M.,Coscia, A.,Musicco, M. The multicenter Italian birth cohort study on incidence and determinants of lower respiratory tract infection hospitalization in infants at 33 weeks GA or more: preliminary results. Early Hum Dev. 2011;87 Suppl 1:S43-6. | Independent variable
1282 | Lanari, M.,Prinelli, F.,Adorni, F.,Di Santo, S.,Faldella, G.,Silvestri, M.,Musicco, M. Maternal milk protects infants against bronchiolitis during the first year of life. Results from an Italian cohort of newborns. Early Hum Dev. 2013;89 Suppl 1:S51-7. | Included for systematic reviews not completed
1283 | Lanari, M.,Prinelli, F.,Adorni, F.,Di Santo, S.,Vandini, S.,Silvestri, M.,Musicco, M. Risk factors for bronchiolitis hospitalization during the first year of life in a multicenter Italian birth cohort. Ital J Pediatr. 2015;41:40. | Included for systematic reviews not completed
1284 | Lancashire, R. J.,Sorahan, T. Breastfeeding and childhood cancer risks: OSCC data. Br J Cancer. 2003;88(7):1035-7. | Dependent variable
1285 | Landaas, S.,Skrede, S.,Steen, J. A. The levels of serum enzymes, plasma proteins and lipids in normal infants and small children. J Clin Chem Clin Biochem. 1981;19(10):1075-80. | Study design
1286 | Lande, B.,Andersen, L. F.,Henriksen, T.,Baerug, A.,Johansson, L.,Trygg, K. U.,Bjorneboe, G. E.,Veierod, M. B. Relations between high ponderal index at birth, feeding practices and body mass index in infancy. Eur J Clin Nutr. 2005;59(11):1241-9. | Included for systematic reviews not completed
1287 | Lane, B. J.,Sellen, V. Bottle caries: a nursing responsibility. Can J Public Health. 1986;77(2):128-30. | Study design
1288 | Lane, D. M.,McConathy, W. J. Changes in the serum lipids and apolipoproteins in the first four weeks of life. Pediatr Res. 1986;20(4):332-7. | Group size
1289 | Langeland, T. A clinical and immunological study of allergy to hen’s egg white. I. A clinical study of egg allergy. Clin Allergy. 1983;13(4):371-82. | Independent variable, Dependent variable
1290 | Langman, M. J. Can epidemiology help us prevent celiac disease?. Gastroenterology. 1986;90(2):489-91. | Study design
1291 | Langnase, K.,Mast, M.,Danielzik, S.,Spethmann, C.,Muller, M. J. Socioeconomic gradients in body weight of German children reverse direction between the ages of 2 and 6 years. J Nutr. 2003;133(3):789-96. | Included for systematic reviews not completed
1292 | Lanting, C. I.,Fidler, V.,Huisman, M.,Touwen, B. C.,Boersma, E. R. Neurological differences between 9-year-old children fed breast-milk or formula-milk as babies. Lancet. 1994;344(8933):1319-22. | Independent variable
1293 | Lanting, C. I.,Patandin, S.,Weisglas-Kuperus, N.,Touwen, B. C.,Boersma, E. R. Breastfeeding and neurological outcome at 42 months. Acta Paediatr. 1998;87(12):1224-9. | Included for systematic reviews not completed
1294 | Laohaviranit L. Milk and health. J Med Assoc Thai. 1985;68:326-9. | Study design
1295 | Lapinleimu, H.,Vukari, J.,Nunikoski, H.,Tuominen, J.,Ronnemaa, T.,Valimaki, I.,Marniemi, J.,Jokinen, E.,Ehnholm, C.,Simell, O. Impact of gender, apolipoprotein E phenotypes, and diet on serum lipids and lipoproteins in infancy. J Pediatr. 1997;131(6):825-32. | Group size
1296 | Larsson, E. Sucking, chewing, and feeding habits and the development of crossbite: a longitudinal study of girls from birth to 3 years of age. Angle Orthod. 2001;71(2):116-9. | Independent variable
1297 | Larsson, J.,Aurelius, G.,Nordberg, L.,Rydelius, P.,Zetterström, R. The role of cumulative observations in identifying children in need of health promotion..including commentary by Glascoe FP. Ambulatory Child Health. 1999;5(3):209-217 9p. | Included for systematic reviews not completed
1298 | Lasekan, J. B.,Ostrom, K. M.,Jacobs, J. R.,Blatter, M. M.,Ndife, L. I.,Gooch, Iii W. M.,Cho, S. Growth of newborn, term infants fed soy formulas for 1 year. Clinical Pediatrics. 1999;38(10):563-571. | Included for systematic reviews not completed
1299 | Laskey, M. A.,de Bono, S.,Smith, E. C.,Prentice, A. Influence of birth weight and early diet on peripheral bone in premenopausal Cambridge women: a pQCT study. J Musculoskelet Neuronal Interact. 2007;7(1):83. | Study design
1300 | Lau, Y. L.,Karlberg, J.,Yeung, C. Y. Prevalence of and factors associated with childhood asthma in Hong Kong. Acta Paediatr. 1995;84(7):820-2. | Study design
1301 | Laubereau, B.,Brockow, I.,Zirngibl, A.,Koletzko, S.,Gruebl, A.,von Berg, A.,Filipiak-Pittroff, B.,Berdel, D.,Bauer, C. P.,Reinhardt, D.,Heinrich, J.,Wichmann, H. E. Effect of breast-feeding on the development of atopic dermatitis during the first 3 years of life--results from the GINI-birth cohort study. J Pediatr. 2004;144(5):602-7. | Independent variable
1302 | Lauer, J. A.,Betran, A. P.,Barros, A. J.,de Onis, M. Deaths and years of life lost due to suboptimal breast-feeding among children in the developing world: a global ecological risk assessment. Public Health Nutr. 2006;9(6):673-85. | Study design, Country
1303 | Lauver, M. A.,Hizon, L.,Bulla, A.,Connell, C.,Wagoner, B. Infant feeding practices: the effect on six month weight. J Kans Med Soc. 1981;82(9):403-6. | Group size
1304 | Lauzon-Guillain, Bd,Wijndaele, K.,Clark, M.,Acerini, C. L.,Hughes, I. A.,Dunger, D. B.,Wells, J. C.,Ong, K. K. Breastfeeding and infant temperament at age three months. PLoS One. 2012;7(1):e29326. | Study design
1305 | Lawlor, D. A.,Najman, J. M.,Batty, G. D.,O’Callaghan, M. J.,Williams, G. M.,Bor, W. Early life predictors of childhood intelligence: findings from the Mater-University study of pregnancy and its outcomes. Paediatr Perinat Epidemiol. 2006;20(2):148-62. | Included for systematic reviews not completed
1306 | Lawlor, D. A.,Najman, J. M.,Sterne, J.,Williams, G. M.,Ebrahim, S.,Davey Smith, G. Associations of parental, birth, and early life characteristics with systolic blood pressure at 5 years of age: findings from the Mater-University study of pregnancy and its outcomes. Circulation. 2004;110(16):2417-23. | Independent variable
1307 | Lawlor, D. A.,Riddoch, C. J.,Page, A. S.,Andersen, L. B.,Wedderkopp, N.,Harro, M.,Stansbie, D.,Smith, G. D. Infant feeding and components of the metabolic syndrome: findings from the European Youth Heart Study. Arch Dis Child. 2005;90(6):582-8. | Study design, Independent variable
1308 | Lawrence, R. A. Breast-feeding trends: a cause for action. Pediatrics. 1991;88(4):867-8. | Study design
1309 | Lawrence, R. A. Can we expect greater intelligence from human milk feedings?. Birth. 1992;19(2):105-6. | Study design
1310 | Lawrence, R. A. Promotion of Breastfeeding Intervention Trial (PROBIT) a randomized trial in the Republic of Belarus. J Pediatr. 2001;139(1):164-5. | Study design
1311 | Layte, R.,Bennett, A.,McCrory, C.,Kearney, J. Social class variation in the predictors of rapid growth in infancy and obesity at age 3 years. Int J Obes (Lond). 2014;38(1):82-90. | Included for systematic reviews not completed
1312 | Lazerov, J.,Ervin, C. Promoting breastfeeding: breastfeeding and population health. Breastfeed Med. 2011;6:305-6. | Study design
1313 | Leary SD, Lawlor DA, Davey Smith G, Brion MJ, Ness AR. Behavioural early-life exposures and body composition at age 15 years. Nutrition and Diabetes. 2015;5(2)e150. | Included for systematic reviews not completed
1314 | Lee, B. Breastfeeding. J R Soc Med. 1995;88(9):537p-538p. | Study design
1315 | Lee, H. A.,Kim, Y. J.,Lee, H.,Gwak, H. S.,Hong, Y. S.,Kim, H. S.,Park, E. A.,Cho, S. J.,Ha, E. H.,Park, H. The preventive effect of breast-feeding for longer than 6 months on early pubertal development among children aged 7-9 years in Korea. Public Health Nutr. 2015:1-8. | Included for systematic reviews not completed
1316 | Lee, L. C.,Pratt, C. A.,DeLaski-Smith, D.,Karabenick, S. A. The growth patterns of American-born Chinese infants. Nutrition Research. 1999;19(5):697-708. | Group size
1317 | Leeson, C. P.,Kattenhorn, M.,Deanfield, J. E.,Lucas, A. Duration of breast feeding and arterial distensibility in early adult life: population based study. BMJ. 2001;322(7287):643-7. | Study design
1318 | Legovic, M.,Ostric, L. The effects of feeding methods on the growth of the jaws in infants. ASDC J Dent Child. 1991;58(3):253-5. | Study design
1319 | Lemons PK,Kochanczyk M,Lemons JA. Breast-feeding the newborn. J Indiana State Med Assoc. 1980;73:373-8. | Study design
1320 | Lenguerrand, E.,Harding, S. P46 Ethnic differences in pace of growth between birth and 5 years: results from the millennium cohort study. Journal of Epidemiology & Community Health. 2010;64:A51-A51 1p. | Peer review
1321 | Leonard, W. R.,Dewalt, K. M.,Stansbury, J. P.,McCaston, M. K. Influence of dietary quality on the growth of highland and coastal Ecuadorian children. Am J Hum Biol. 2000;12(6):825-837. | Included for systematic reviews not completed
1322 | Lerman, Y.,Slepon, R.,Cohen, D. Epidemiology of acute diarrheal diseases in children in a high standard of living rural settlement in Israel. Pediatr Infect Dis J. 1994;13(2):116-22. | Study design
1323 | Leung, E. Y.,Au, K. Y.,Cheng, S. S.,Kok, S. Y.,Lui, H. K.,Wong, W. C. Practice of breastfeeding and factors that affect breastfeeding in Hong Kong. Hong Kong Med J. 2006;12(6):432-6. | Dependent variable
1324 | Leung, G. M.,Lam, T. H.,Ho, L. M.,Lau, Y. L. Health consequences of breast-feeding: doctors’ visits and hospitalizations during the first 18 months of life in Hong Kong Chinese infants. Epidemiology. 2005;16(3):328-35. | Included for systematic reviews not completed
1325 | Leung, S. S. F.,Davies, D. P.,Lui, S.,Lo, L.,Yuen, P.,Swaminathan, R. Iron deficiency is uncommon in healthy Hong Kong infants at 18 months. Journal of Tropical Pediatrics. 1988;34(3):100-103. | Independent variable, Dependent variable
1326 | Leung, S. S.,Peng, C. X.,Xu, Y. Y.,Liu, K. M.,Quan, X. J.,Lui, S.,Davies, D. P. Comparative study of growth of Chinese infants: Hong Kong versus Guangzhou. J Trop Pediatr. 1994;40(3):166-71. | Independent variable
1327 | Leung, S.,Davies, D. P. Infant feeding and growth of Chinese infants: birth to 2 years. Paediatr Perinat Epidemiol. 1994;8(3):301-13. | Independent variable
1328 | Leventakou, V.,Roumeliotaki, T.,Koutra, K.,Vassilaki, M.,Mantzouranis, E.,Bitsios, P.,Kogevinas, M.,Chatzi, L. Breastfeeding duration and cognitive, language and motor development at 18 months of age: Rhea mother-child cohort in Crete, Greece. J Epidemiol Community Health. 2015;69(3):232-9. | Included for systematic reviews not completed
1329 | Leventhal, J. M.,Shapiro, E. D.,Aten, C. B.,Berg, A. T.,Egerter, S. A. Does breast-feeding protect against infections in infants less than 3 months of age?. Pediatrics. 1986;78(5):896-903. | Included for systematic reviews not completed
1330 | Lever, R. The role of food in atopic eczema. J Am Acad Dermatol. 2001;45(1 Suppl):S57-60. | Study design
1331 | Levine, O. S.,Farley, M.,Harrison, L. H.,Lefkowitz, L.,McGeer, A.,Schwartz, B. Risk factors for invasive pneumococcal disease in children: a population-based case-control study in North America. Pediatrics. 1999;103(3):E28. | Study design, Independent variable
1332 | Lewando-Hundt, G.,Forman, M. R. Autonomy, access and care: a study of Palestinian Bedouin of the Negev of Israel. Social Sciences in Health. 1997;3(2):83-95 13p. | Independent variable, Dependent variable
1333 | Lewis, J. K. Anderson M. Willeitner A. Powdered Versus Liquid Human Milk Fortifier: A Blinded, Randomized, Controlled Trial. Pediatric Academic Societies Annual Meeting. 2011. | Peer review
1334 | Lewis, S.,Butland, B.,Strachan, D.,Bynner, J.,Richards, D.,Butler, N.,Britton, J. Study of the aetiology of wheezing illness at age 16 in two national British birth cohorts. Thorax. 1996;51(7):670-6. | Study design, Independent variable
1335 | L’Hoir, M. P.,Engelberts, A. C.,van Well, G. T.,Damste, P. H.,Idema, N. K.,Westers, P.,Mellenbergh, G. J.,Wolters, W. H.,Huber, J. Dummy use, thumb sucking, mouth breathing and cot death. Eur J Pediatr. 1999;158(11):896-901. | Included for systematic reviews not completed
1336 | l’Hoir, M. P.,Engelberts, A. C.,van Well, G. T.,Westers, P.,Mellenbergh, G. J.,Wolters, W. H.,Huber, J. Case-control study of current validity of previously described risk factors for SIDS in The Netherlands. Arch Dis Child. 1998;79(5):386-93. | Included for systematic reviews not completed
1337 | Li, C.,Goran, M. I.,Kaur, H.,Nollen, N.,Ahluwalia, J. S. Developmental trajectories of overweight during childhood: role of early life factors. Obesity (Silver Spring). 2007;15(3):760-71. | Included for systematic reviews not completed
1338 | Li, C.,Kaur, H.,Choi, W. S.,Huang, T. T.,Lee, R. E.,Ahluwalia, J. S. Additive interactions of maternal prepregnancy BMI and breast-feeding on childhood overweight. Obes Res. 2005;13(2):362-71. | Included for systematic reviews not completed
1339 | Li, J.,Dykman, R. A.,Jing, H.,Gilchrist, J. M.,Badger, T. M.,Pivik, R. T. Cortical responses to speech sounds in 3- and 6-month-old infants fed breast milk, milk formula, or soy formula. Dev Neuropsychol. 2010;35(6):762-84. | Included for systematic reviews not completed
1340 | Li, L.,Kleinman, K.,Gillman, M. W. A comparison of confounding adjustment methods with an application to early life determinants of childhood obesity. J Dev Orig Health Dis. 2014;5(6):435-47. | Study design, Independent variable
1341 | Li, L.,Manor, O.,Power, C. Early environment and child-to-adult growth trajectories in the 1958 British birth cohort. Am J Clin Nutr. 2004;80(1):185-92. | Independent variable
1342 | Li, L.,Power, C. Influences on childhood height: comparing two generations in the 1958 British birth cohort. Int J Epidemiol. 2004;33(6):1320-8. | Independent variable
1343 | Li, N.,Strobino, D.,Ahmed, S.,Minkovitz, C. S. Is there a healthy foreign born effect for childhood obesity in the United States?. Matern Child Health J. 2011;15(3):310-23. | Included for systematic reviews not completed
1344 | Li, R.,Dee, D.,Li, C. M.,Hoffman, H. J.,Grummer-Strawn, L. M. Breastfeeding and risk of infections at 6 years. Pediatrics. 2014;134 Suppl 1:S13-20. | Included for systematic reviews not completed
1345 | Li, R.,Fein, S. B.,Grummer-Strawn, L. M. Association of breastfeeding intensity and bottle-emptying behaviors at early infancy with infants’ risk for excess weight at late infancy. Pediatrics. 2008;122 Suppl 2:S77-84. | Included for systematic reviews not completed
1346 | Li, R.,Fein, S. B.,Grummer-Strawn, L. M. Do infants fed from bottles lack self-regulation of milk intake compared with directly breastfed infants?. Pediatrics. 2010;125(6):e1386-93. | Dependent variable
1347 | Li, R.,Magadia, J.,Fein, S. B.,Grummer-Strawn, L. M. Risk of bottle-feeding for rapid weight gain during the first year of life. Arch Pediatr Adolesc Med. 2012;166(5):431-6. | Included for systematic reviews not completed
1348 | Li, S. C.,Kuo, S. C.,Hsu, Y. Y.,Lin, S. J.,Chen, P. C.,Chen, Y. C. Effect of Breastfeeding Duration on Infant Growth Until 18 Months of Age: A National Birth Cohort Study. Journal of Experimental and Clinical Medicine. 2010;2(4):165-172. | Included for systematic reviews not completed
1349 | Li, Y.,Navia, J. M.,Caufield, P. W. Colonization by mutans streptococci in the mouths of 3- and 4-year-old Chinese children with or without enamel hypoplasia. Arch Oral Biol. 1994;39(12):1057-62. | Study design
1350 | Liao, S. L.,Lai, S. H.,Yeh, K. W.,Huang, Y. L.,Yao, T. C.,Tsai, M. H.,Hua, M. C.,Huang, J. L.. Exclusive breastfeeding is associated with reduced cow’s milk sensitization in early childhood. Pediatr Allergy Immunol. 2014;25(5):456-61. | Dependent variable
1351 | Libraty, D. H.,Capeding, R. Z.,Obcena, A.,Brion, J. D.,Tallo, V. Breastfeeding During Early Infancy is Associated with a Lower Incidence of Febrile Illnesses. Open Pediatr Med Journal. 2013;7:40-41. | Dependent variable, Country
1352 | Liebrechts-Akkerman, G.,Lao, O.,Liu, F.,Van Sleuwen, B. E.,Engelberts, A. C.,L’Hoir, M. P.,Tiemeier, H. W.,Kayser, M. Postnatal parental smoking: An important risk factor for SIDS. European Journal of Pediatrics. 2011;170(10):1281-1291. | Included for systematic reviews not completed
1353 | Lima, A. A.,Moore, S. R.,Barboza, M. S., Jr.,Soares, A. M.,Schleupner, M. A.,Newman, R. D.,Sears, C. L.,Nataro, J. P.,Fedorko, D. P.,Wuhib, T.,Schorling, J. B.,Guerrant, R. L. Persistent diarrhea signals a critical period of increased diarrhea burdens and nutritional shortfalls: a prospective cohort study among children in northeastern Brazil. J Infect Dis. 2000;181(5):1643-51. | Included for systematic reviews not completed
1354 | Lin, H.,Sun, L.,Lin, J.,He, J.,Deng, A.,Kang, M.,Zeng, H.,Ma, W.,Zhang, Y. Protective effect of exclusive breastfeeding against hand, foot and mouth disease. BMC Infect Dis. 2014;14:645. | Study design, Dependent variable
1355 | Lind, J. N.,Li, R.,Perrine, C. G.,Schieve, L. A. Breastfeeding and later psychosocial development of children at 6 years of age. Pediatrics. 2014;134 Suppl 1:S36-41. | Included for systematic reviews not completed
1356 | Lindberg, S. M.,Adams, A. K.,Prince, R. J. Early predictors of obesity and cardiovascular risk among American Indian children. Matern Child Health J. 2012;16(9):1879-86. | Included for systematic reviews not completed
1357 | Lindenberg, C. S.,Artola, R. C.,Estrada, V. J. Determinants of early infant weaning: a multivariate approach. Int J Nurs Stud. 1990;27(1):35-41. | Country
1358 | Lindfors, A. T.,Danielsson, L.,Enocksson, E.,Johansson, S. G.,Westin, S. Allergic symptoms up to 4-6 years of age in children given cow milk neonatally. A prospective study. Allergy. 1992;47(3):207-11. | Independent variable
1359 | Lindfors, A.,Enocksson, E. Development of atopic disease after early administration of cow milk formula. Allergy. 1988;43(1):11-6. | Independent variable
1360 | Linhares Rda, S.,Gigante, D. P.,de Barros, F. C.,Horta, B. L. Carotid intima-media thickness at age 30, birth weight, accelerated growth during infancy and breastfeeding: a birth cohort study in Southern Brazil. PLoS One. 2015;10(1):e0115166. | Independent variable
1361 | Linhares, A. C.,Gabbay, Y. B.,Freitas, R. B.,da Rosa, E. S.,Mascarenhas, J. D.,Loureiro, E. C. Longitudinal study of rotavirus infections among children from Belem, Brazil. Epidemiol Infect. 1989;102(1):129-45. | Included for systematic reviews not completed
1362 | Linneberg, A.,Simonsen, J. B.,Petersen, J.,Stensballe, L. G.,Benn, C. S. Differential effects of risk factors on infant wheeze and atopic dermatitis emphasize a different etiology. J Allergy Clin Immunol. 2006;117(1):184-9. | Independent variable
1363 | Lionetti, E.,Castellaneta, S.,Francavilla, R.,Pulvirenti, A.,Tonutti, E.,Amarri, S.,Barbato, M.,Barbera, C.,Barera, G.,Bellantoni, A.,Castellano, E.,Limongelli, M. G.,Pellegrino, S.,Polloni, C.,Ughi, C.,Zuin, G.,Guariso, G.,Fasano, A.,Catassi, C. Infant feeding pattern, HLA status, and prevalence of celiac disease. Digestive and liver disease. 2014;46:e75-e76. | Study design
1364 | Lionetti, E.,Castellaneta, S.,Pulvirenti, A.,Tonutti, E.,Francavilla, R.,Fasano, A.,Catassi, C. Prevalence and natural history of potential celiac disease in at-family-risk infants prospectively investigated from birth. J Pediatr. 2012;161(5):908-14. | Group size
1365 | Lipsman, S.,Dewey, K. G.,Lonnerdal, B. Breast-feeding among teenage mothers: milk composition, infant growth, and maternal dietary intake. J Pediatr Gastroenterol Nutr. 1985;4(3):426-34. | Group size
1366 | Litmanovitz, I.,Davidson, K.,Eliakim, A.,Regev, R. H.,Dolfin, T.,Arnon, S.,Bar-Yoseph, F.,Goren, A.,Lifshitz, Y.,Nemet, D. High Beta-palmitate formula and bone strength in term infants: a randomized, double-blind, controlled trial. Calcif Tissue Int. 2013;92(1):35-41. | Group size
1367 | Little, R. E.,Lambert, M. D., 3rd,Worthington-Roberts, B.,Ervin, C. H. Maternal smoking during lactation: relation to infant size at one year of age. Am J Epidemiol. 1994;140(6):544-54. | Included for systematic reviews not completed
1368 | Liu, J. Neglected problem: nursing bottle syndrome. Dentistry (Loma Linda). 1990;3(2):57-8. | Study design
1369 | Liu, J.,Leung, P.,Yang, A. Breastfeeding and active bonding protects against children’s internalizing behavior problems. Nutrients. 2014;6(1):76-89. | Study design, Independent variable
1370 | Liu, Y. Q.,Qian, Z.,Wang, J.,Lu, T.,Lin, S.,Zeng, X. W.,Liu, R. Q.,Zhu, Y.,Qin, X. D.,Yuan, P.,Zhou, Y.,Li, M.,Hao, Y. T.,Dong, G. H. Breastfeeding modifies the effects of environment tobacco smoke exposure on respiratory diseases and symptoms in Chinese children: the Seven Northeast Cities Study. Indoor Air. 2015. | Study design
1371 | Livingstone, V. Failure to thrive while breastfeeding. Breastfeed Med. 2006;1(2):108-11. | Study design
1372 | Livny, A.,Assali, R.,Sgan-Cohen, H. D. Early Childhood Caries among a Bedouin community residing in the eastern outskirts of Jerusalem. BMC Public Health. 2007;7:167. | Study design
1373 | Lnnerdal, B.,Timby, N.,Domellf, M.,Domellf, E.,Hernell, O. Supplementation of infant formula with milk fat globule membranes improves cognitive performance and reduces infections in formula-fed infants. FASEB journal. 2014;28(1 suppl. 1). | Peer review
1374 | Lo, G. L. The use of comforters and dental caries in the Singaporean preschool children. Singapore Dent J. 1985;10(1):21-4. | Independent variable
1375 | Lodge, C. J.,Zaloumis, S.,Lowe, A. J.,Gurrin, L. C.,Matheson, M. C.,Axelrad, C.,Bennett, C. M.,Hill, D. J.,Hosking, C. S.,Svanes, C.,Abramson, M. J.,Allen, K. J.,Dharmage, S. C. Early-life risk factors for childhood wheeze phenotypes in a high-risk birth cohort. J Pediatr. 2014;164(2):289-94 e1-2. | Dependent variable
1376 | Lodinova, R.,Jouja, V.,Vinsova, N.,Vocel, J.,Melkova, J. New attempts and possibilities in prevention and treatment of intestinal coli-infections in infants. Czech Med. 1980;3(1):47-58. | Study design, Dependent variable
1377 | Lodinova-Zadnikova, R.,Tlaskalova, H.,Bartakova, Z. The antibody response in infants after colonization of the intestine with E. coli O83. Artificial colonization used as a prevention against nosocomial infections. Adv Exp Med Biol. 1991;310:329-35. | Study design, Health status
1378 | Loeb H,Mozin MJ. Prevention of chronic diarrhea: nutritional implications. J Pediatr Gastroenterol Nutr. 1983;2 Suppl 1:S328-34. | Study design
1379 | Lombeck, I.,Fuchs, A. Zinc and copper in infants fed breast-milk or different formula. Eur J Pediatr. 1994;153(10):770-6. | Included for systematic reviews not completed
1380 | Long, K. Z.,Wood, J. W.,Vasquez Gariby, E.,Weiss, K. M.,Mathewson, J. J.,de la Cabada, F. J.,DuPont, H. L.,Wilson, R. A. Proportional hazards analysis of diarrhea due to enterotoxigenic Escherichia coli and breast feeding in a cohort of urban Mexican children. Am J Epidemiol. 1994;139(2):193-205. | Included for systematic reviews not completed
1381 | Long, K.,Vasquez-Garibay, E.,Mathewson, J.,de la Cabada, J.,DuPont, H. The impact of infant feeding patterns on infection and diarrheal disease due to enterotoxigenic Escherichia coli. Salud Publica Mex. 1999;41(4):263-70. | Independent variable
1382 | Long, S. A.,Bugg, K. Can’t we all just get along?. J Hum Lact. 2015;31(1):29-31. | Study design
1383 | Lonnerdal, B.,Chen, C. L. Effects of formula protein level and ratio on infant growth, plasma amino acids and serum trace elements. I. Cow’s milk formula. Acta Paediatr Scand. 1990;79(3):257-65. | Included for systematic reviews not completed
1384 | Lonnerdal, B.,Havel, P. J. Serum leptin concentrations in infants: effects of diet, sex, and adiposity. Am J Clin Nutr. 2000;72(2):484-9. | Independent variable
1385 | Lonnerdal, B.,Hernell, O. Effects of feeding ultrahigh-temperature (UHT)-treated infant formula with different protein concentrations or powdered formula, as compared with breast-feeding, on plasma amino acids, hematology, and trace element status. Am J Clin Nutr. 1998;68(2):350-6. | Included for systematic reviews not completed
1386 | Lonnerdal, B.,Hernell, O. Iron, zinc, copper and selenium status of breast-fed infants and infants fed trace element fortified milk-based infant formula. Acta Paediatr. 1994;83(4):367-73. | Independent variable
1387 | Lonnerdal, B.,Kvistgaard, A. S.,Peerson, J. M.,Donovan, S. M.,Peng, Y. M. Growth, Nutrition and Cytokine Response of Breast-Fed Infants and Infants Fed Formula with Added Bovine Osteopontin. J Pediatr Gastroenterol Nutr. 2015. | Included for systematic reviews not completed
1388 | Lopez Bravo, I. M.,Sepulveda, H.,Valdes, I. Acute respiratory illnesses in the first 18 months of life. Rev Panam Salud Publica. 1997;1(1):9-17. | Included for systematic reviews not completed
1389 | Lopez Bravo, I.,Cabiol, C.,Arcuch, S.,Rivera, E.,Vargas, S. Breast-feeding, weight gains, diarrhea, and malnutrition in the first year of life. Bull Pan Am Health Organ. 1984;18(2):151-63. | Included for systematic reviews not completed
1390 | Lopez Del Valle, L. M.,Singh, G. D.,Feliciano, N.,Machuca Mdel, C. Associations between a history of breast feeding, malocclusion and parafunctional habits in Puerto Rican children. P R Health Sci J. 2006;25(1):31-4. | Study design
1391 | López, N.,De Barros-Mazón, S.,Dos Santos Vilela, M. M.,Silva, C. M.,Ribeiro, J. D. Genetic and environmental influences on atonic immune response in early life. Journal of Investigational Allergology and Clinical Immunology. 1999;9(6):392-398. | Dependent variable
1392 | Lopez, N.,de Barros-Mazon, S.,Vilela, M. M.,Silva, C. M.,Ribeiro, J. D. Genetic and environmental influences on atopic immune response in early life. J Investig Allergol Clin Immunol. 1999;9(6):392-8. | Dependent variable
1393 | Lopez-Alarcon, M.,Villalpando, S.,Fajardo, A. Breast-feeding lowers the frequency and duration of acute respiratory infection and diarrhea in infants under six months of age. J Nutr. 1997;127(3):436-43. | Included for systematic reviews not completed
1394 | Losonsky, G. A.,D’Alessandra de Rimer, H. Rotavirus specific breast milk antibody in two populations and possible correlates of protection. Adv Exp Med Biol. 1991;310:265-9. | Study design, Dependent variable
1395 | Louzada, M. L.,Campagnolo, P. D.,Rauber, F.,Vitolo, M. R. Long-term effectiveness of maternal dietary counseling in a low-income population: a randomized field trial. Pediatrics. 2012;129(6):e1477-84. | Independent variable
1396 | Lowe, A. J.,Carlin, J. B.,Bennett, C. M.,Abramson, M. J.,Hosking, C. S.,Hill, D. J.,Dharmage, S. C. Atopic disease and breast-feeding--cause or consequence?. J Allergy Clin Immunol. 2006;117(3):682-7. | Independent variable
1397 | Lozoff, B.,Wolf, A. W.,Jimenez, E. Iron-deficiency anemia and infant development: effects of extended oral iron therapy. J Pediatr. 1996;129(3):382-9. | Included for systematic reviews not completed
1398 | Lu, R.,Costello, A. Failure to exclusively breastfeed and the risk of early infant mortality due to infectious disease in poor communities in Lima, Peru. J Trop Pediatr. 2000;46(5):309-11. | Included for systematic reviews not completed
1399 | Lubis, I. Z.,Sinuhaji, A. B.,Sebayang, T.,Lubis, M.,Barus, N.,Sutanto, A. H. Factors influencing the duration of infantile diarrhea. Paediatr Indones. 1985;25(9-10):175-89. | Country
1400 | Lucas, A.,Boyes, S.,Bloom, S. R.,Aynsley-Green, A. Metabolic and endocrine responses to a milk feed in six-day-old term infants: differences between breast and cow’s milk formula feeding. Acta Paediatr Scand. 1981;70(2):195-200. | Study design, Dependent variable
1401 | Lucas, A.,Ewing, G.,Roberts, S. B.,Coward, W. A. How much energy does the breast fed infant consume and expend?. Br Med J (Clin Res Ed). 1987;295(6590):75-7. | Group size
1402 | Lucas, A.,Lockton, S.,Davies, P. S. Randomised trial of a ready-to-feed compared with powdered formula. Arch Dis Child. 1992;67(7):935-9. | Group size
1403 | Lucas, A.,Stafford, M.,Morley, R.,Abbott, R.,Stephenson, T.,MacFadyen, U.,Elias-Jones, A.,Clements, H. Efficacy and safety of long-chain polyunsaturated fatty acid supplementation of infant-formula milk: a randomised trial. Lancet. 1999;354(9194):1948-54. | Included for systematic reviews not completed
1404 | Luccioli, S.,Zhang, Y.,Verrill, L.,Ramos-Valle, M.,Kwegyir-Afful, E. Infant feeding practices and reported food allergies at 6 years of age. Pediatrics. 2014;134 Suppl 1:S21-8. | Independent variable
1405 | Ludvigsson, J. Cow-milk-free diet during last trimester of pregnancy does not influence diabetes-related autoantibodies in nondiabetic children. Ann N Y Acad Sci. 2003;1005:275-8. | Dependent variable
1406 | Ludvigsson, J. F.,Mostrom, M.,Ludvigsson, J.,Duchen, K. Exclusive breastfeeding and risk of atopic dermatitis in some 8300 infants. Pediatr Allergy Immunol. 2005;16(3):201-8. | Study design
1407 | Lulic-Dukic, O.,Juric, H.,Dukic, W.,Glavina, D. Factors predisposing to early childhood caries (ECC) in children of pre-school age in the city of Zagreb, Croatia. Coll Antropol. 2001;25(1):297-302. | Study design
1408 | Lumia, M.,Takkinen, H. M.,Luukkainen, P.,Kaila, M.,Lehtinen-Jacks, S.,Nwaru, B. I.,Tuokkola, J.,Niemela, O.,Haapala, A. M.,Ilonen, J.,Simell, O.,Knip, M.,Veijola, R.,Virtanen, S. M. Food consumption and risk of childhood asthma. Pediatr Allergy Immunol. 2015. | Independent variable
1409 | Lunardelli, S. E.,Peres, M. A. Breast-feeding and other mother-child factors associated with developmental enamel defects in the primary teeth of Brazilian children. J Dent Child (Chic). 2006;73(2):70-8. | Included for systematic reviews not completed
1410 | Lundberg, G. D. Does breast-feeding improve child cognitive development?. MedGenMed Medscape General Medicine. 2008;10(8). | Study design
1411 | Lundqvist-Persson, C. Correlation between level of self-regulation in the newborn infant and developmental status at two years of age. Acta Paediatrica, International Journal of Paediatrics. 2001;90(3):345-350. | Group size
1412 | Luo, R.,Shi, Y.,Zhou, H.,Yue, A.,Zhang, L.,Sylvia, S.,Medina, A.,Rozelle, S. Anemia and feeding practices among infants in rural Shaanxi Province in China. Nutrients. 2014;6(12):5975-91. | Study design
1413 | Luo,R,Shi,Y,Zhou,H,Yue,A,Zhang,L,Sylvia,S,Medina,A,Rozelle,S,. Anemia and feeding practices among infants in rural Shaanxi Province in China. Nutrients. 2014;6(12):5975-91. | Study design
1414 | Luoma, R.. Environmental allergens and morbidity in atopic and non-atopic families. Acta Paediatr Scand. 1984;73(4):448-53. | Included for systematic reviews not completed
1415 | Luopajarvi, K.,Savilahti, E.,Virtanen, S. M.,Ilonen, J.,Knip, M.,Akerblom, H. K.,Vaarala, O. Enhanced levels of cow’s milk antibodies in infancy in children who develop type 1 diabetes later in childhood. Pediatr Diabetes. 2008;9(5):434-41. | Group size
1416 | Lutter, C. K. Breastfeeding promotion--is its effectiveness supported by scientific evidence and global changes in breastfeeding behaviors?. Adv Exp Med Biol. 2000;478:355-68. | Study design
1417 | Lyall, J. Growing problems. Nurs Times. 1991;87(24):22-3. | Study design
1418 | Ma, D. Q.,Jones, G. Clinical risk factors but not bone density are associated with prevalent fractures in prepubertal children. J Paediatr Child Health. 2002;38(5):497-500. | Study design
1419 | Ma, J. Q.,Zhou, L. L.,Hu, Y. Q.,Liu, J. R.,Liu, S. S.,Zhang, J.,Sheng, X. Y. A summary index of infant and child feeding practices is associated with child growth in urban Shanghai. BMC Public Health. 2012;12:568. | Included for systematic reviews not completed
1420 | MacDonald, L. D.,Gibson, R. S.,Miles, J. E. Changes in hair zinc and copper concentrations of breast fed and bottle fed infants during the first six months. Acta Paediatr Scand. 1982;71(5):785-9. | Group size
1421 | Macdonald, P. D.,Ross, S. R.,Grant, L.,Young, D. Neonatal weight loss in breast and formula fed infants. Arch Dis Child Fetal Neonatal Ed. 2003;88(6):F472-6. | Included for systematic reviews not completed
1422 | MacIntyre, E. A.,Karr, C. J.,Koehoorn, M.,Demers, P.,Tamburic, L.,Lencar, C.,Brauer, M. Otitis media incidence and risk factors in a population-based birth cohort. Paediatrics and Child Health. 2010;15(7):437-442. | Included for systematic reviews not completed
1423 | Macoun, E. The NSW Health Breastfeeding Project. N S W Public Health Bull. 2005;16(3-4):62. | Study design
1424 | Madhavapeddi, R.,Ramachandran, P. Growth and morbidity of breastfed infants whose mothers were using combination pills. Breastfeeding Review. 1990;2(2):66-68 3p. | Country
1425 | Madhavapeddi, R.,Ramachandran, P. Growth of urban breastfed infants from low socio-economic group. J Trop Pediatr. 1993;39(6):328-31. | Country
1426 | Madsen, A. L.,Larnkjaer, A.,Molgaard, C.,Michaelsen, K. F. IGF-I and IGFBP-3 in healthy 9 month old infants from the SKOT cohort: breastfeeding, diet, and later obesity. Growth Horm IGF Res. 2011;21(4):199-204. | Study design, Independent variable
1427 | Magalhaes, T. C.,Vieira, S. A.,Priore, S. E.,Ribeiro, A. Q.,Lamounier, J. A.,Franceschini, S. C.,Sant’Ana, L. F. Exclusive breastfeeding and other foods in the first six months of life: effects on nutritional status and body composition of Brazilian children. ScientificWorldJournal. 2012;2012:468581. | Included for systematic reviews not completed
1428 | Magana Cardenas, A.,Padilla Gonzalez, L. M.,Garcia de Alba, J. E.,Troyo San Roman, R.,Delgado Becerra, A. Some epidemiological aspects of maternal breast-feeding in a population entitled to social welfare services in Mexico. Bull Pan Am Health Organ. 1981;15(2):139-47. | Dependent variable
1429 | Magnus, M. C.,DeRoo, L. A.,Haberg, S. E.,Magnus, P.,Nafstad, P.,Nystad, W.,London, S. J. Prospective study of maternal alcohol intake during pregnancy or lactation and risk of childhood asthma: the Norwegian Mother and Child Cohort Study. Alcohol Clin Exp Res. 2014;38(4):1002-11. | Independent variable
1430 | Magnusson, C. G. Cord serum IgE in relation to family history and as predictor of atopic disease in early infancy. Allergy. 1988;43(4):241-51. | Study design, Dependent variable
1431 | Mai, X. M.,Becker, A. B.,Sellers, E. A.,Liem, J. J.,Kozyrskyj, A. L. The relationship of breast-feeding, overweight, and asthma in preadolescents. J Allergy Clin Immunol. 2007;120(3):551-6. | Independent variable
1432 | Maisels, M. J.,Gifford, K. Breast-feeding, weight loss, and jaundice. J Pediatr. 1983;102(1):117-8. | Independent variable
1433 | Majeed, R.,Rajar, U. D.,Shaikh, N.,Majeed, F.,Arain, A. A. Risk factors associated with childhood asthma. J Coll Physicians Surg Pak. 2008;18(5):299-302. | Country
1434 | Majorana, A.,Cagetti, M. G.,Bardellini, E.,Amadori, F.,Conti, G.,Strohmenger, L.,Campus, G. Feeding and smoking habits as cumulative risk factors for early childhood caries in toddlers, after adjustment for several behavioral determinants: a retrospective study. BMC Pediatr. 2014;14:45. | Included for systematic reviews not completed
1435 | Makela, J.,Linderborg, K.,Niinikoski, H.,Yang, B.,Lagstrom, H. Breast milk fatty acid composition differs between overweight and normal weight women: the STEPS Study. Eur J Nutr. 2013;52(2):727-35. | Independent variable, Dependent variable
1436 | Mäkelä, J.,Vaarno, J.,Kaljonen, A.,Niinikoski, H.,Lagström, H. Maternal overweight impacts infant feeding patterns - The STEPS Study. European Journal of Clinical Nutrition. 2014;68(1):43-49. | Included for systematic reviews not completed
1437 | Makela, J.,Vaarno, J.,Kaljonen, A.,Niinikoski, H.,Lagstrom, H. Maternal overweight impacts infant feeding patterns--the STEPS Study. Eur J Clin Nutr. 2014;68(1):43-9. | Duplicate
1438 | Maki, M.,Kallonen, K.,Lahdeaho, M. L.,Visakorpi, J. K. Changing pattern of childhood coeliac disease in Finland. Acta Paediatr Scand. 1988;77(3):408-12. | Study design
1439 | Makrides, M. Outcomes for mothers and their babies: do n-3 long-chain polyunsaturated fatty acids and seafoods make a difference?. J Am Diet Assoc. 2008;108(10):1622-6. | Study design
1440 | Makrides, M.,Gibson, R. A.,Simmer, K. The effect of dietary fat on the developing brain. J Paediatr Child Health. 1993;29(6):409-10. | Study design
1441 | Makrides, M.,Hawkes, J. S.,Neumann, M. A.,Gibson, R. A. Nutritional effect of including egg yolk in the weaning diet of breast-fed and formula-fed infants: a randomized controlled trial. Am J Clin Nutr. 2002;75(6):1084-92. | Independent variable
1442 | Makrides, M.,Neumann, M. A.,Jeffrey, B.,Lien, E. L.,Gibson, R. A. A randomized trial of different ratios of linoleic to alpha-linolenic acid in the diet of term infants: effects on visual function and growth. Am J Clin Nutr. 2000;71(1):120-9. | Included for systematic reviews not completed
1443 | Makrides, M.,Neumann, M. A.,Simmer, K.,Gibson, R. A. A critical appraisal of the role of dietary long-chain polyunsaturated fatty acids on neural indices of term infants: a randomized, controlled trial. Pediatrics. 2000;105(1 Pt 1):32-8. | Included for systematic reviews not completed
1444 | Makrides, M.,Neumann, M. A.,Simmer, K.,Gibson, R. A. Dietary long-chain polyunsaturated fatty acids do not influence growth of term infants: A randomized clinical trial. Pediatrics. 1999;104(3 Pt 1):468-75. | Included for systematic reviews not completed
1445 | Makrides, M.,Neumann, M.,Gibson, R. Breast milk docosahexaenoic acid (DHA) and infant outcomes: a randomised clinical trial. Journal of paediatrics and child health. 1997;33(4):A2. | Peer review
1446 | Male, C.,Persson, L. A.,Freeman, V.,Guerra, A.,van’t Hof, M. A.,Haschke, F. Prevalence of iron deficiency in 12-mo-old infants from 11 European areas and influence of dietary factors on iron status (Euro-Growth study). Acta Paediatr. 2001;90(5):492-8. | Included for systematic reviews not completed
1447 | Malek L,Makrides M. 2.8 Nutrition in pregnancy and lactation. World Rev Nutr Diet. 2015;113:127-33. | Peer review
1448 | Malinowska E,Kaczmarski M,Wasilewska J. Total IgE levels and skin test results in children under three years of age with food hypersensitivity. Med Sci Monit. 2002;8:Cr280-7. | Study design, Independent variable
1449 | Mallol-Mesnard, N.,Menegaux, F.,Lacour, B.,Hartmann, O.,Frappaz, D.,Doz, F.,Bertozzi, A. I.,Chastagner, P.,Hemon, D.,Clavel, J. Birth characteristics and childhood malignant central nervous sytem tumors: the ESCALE study (French Society for Childhood Cancer). Cancer Detect Prev. 2008;32(1):79-86. | Dependent variable
1450 | Malloy, M. H.,Berendes, H. Does breast-feeding influence intelligence quotients at 9 and 10 years of age?. Early Hum Dev. 1998;50(2):209-17. | Study design, Independent variable
1451 | Malta AL. The Optimal Duration of Exclusive Breastfeeding for Physical Growth. Nutr Perspect. 2015;38(4):21-33. | Study design
1452 | Manco, M.,Alterio, A.,Bugianesi, E.,Ciampalini, P.,Mariani, P.,Finocchi, M.,Agostoni, C.,Nobili, V. Insulin dynamics of breast- or formula-fed overweight and obese children. Journal of the American College of Nutrition. 2011;30(1):29-38. | Study design
1453 | Mandel, E. M.,Doyle, W. J.,Winther, B.,Alper, C. M. The incidence, prevalence and burden of OM in unselected children aged 1-8 years followed by weekly otoscopy through the “common cold” season. Int J Pediatr Otorhinolaryngol. 2008;72(4):491-9. | Included for systematic reviews not completed
1454 | Mandhane, P. J.,Greene, J. M.,Sears, M. R. Interactions between breast-feeding, specific parental atopy, and sex on development of asthma and atopy. J Allergy Clin Immunol. 2007;119(6):1359-66. | Independent variable
1455 | Mandic, Z.,Piricki, A. P.,Kenjeric, D.,Hanicar, B.,Tanasic, I. Breast vs. bottle: differences in the growth of Croatian infants. Matern Child Nutr. 2011;7(4):389-96. | Independent variable
1456 | Mangskau, K. Baby bottle tooth decay: a problem affecting young children in North Dakota. Northwest Dent. 1991;70(6):25. | Study design
1457 | Manjrekar, C.,Vishalakshi, M. P.,Begum, N. J.,Padma, G. N. Breast feeding ability of undernourished mothers and physical development of their infants during 0-1 year. Indian Pediatr. 1985;22(11):801-9. | Country
1458 | Maranhao, H. S.,Medeiros, M. C.,Scaletsky, I. C.,Fagundes-Neto, U.,Morais, M. B. The epidemiological and clinical characteristics and nutritional development of infants with acute diarrhoea, in north-eastern Brazil. Ann Trop Med Parasitol. 2008;102(4):357-65. | Independent variable
1459 | Marini, A.,Agosti, M.,Motta, G.,Mosca, F. Effects of a dietary and environmental prevention programme on the incidence of allergic symptoms in high atopic risk infants: three years’ follow-up. Acta Paediatr Suppl. 1996;414:1-21. | Independent variable
1460 | Marmot, M. G.,Page, C. M.,Atkins, E.,Douglas, J. W. Effect of breast-feeding on plasma cholesterol and weight in young adults. J Epidemiol Community Health. 1980;34(3):164-7. | Independent variable
1461 | Marques, R. C.,Dorea, J. G.,Bernardi, J. V.,Bastos, W. R.,Malm, O. Maternal fish consumption in the nutrition transition of the Amazon Basin: growth of exclusively breastfed infants during the first 5 years. Ann Hum Biol. 2008;35(4):363-77. | Included for systematic reviews not completed
1462 | Marques, R. C.,Dorea, J. G.,Bernardi, J. V.,Bastos, W. R.,Malm, O. Prenatal and postnatal mercury exposure, breastfeeding and neurodevelopment during the first 5 years. Cogn Behav Neurol. 2009;22(2):134-41. | Independent variable
1463 | Marques, R. C.,Dorea, J. G.,Leao, R. S.,Dos Santos, V. G.,Bueno, L.,Marques, R. C.,Brandao, K. G.,Palermo, E. F.,Guimaraes, J. R. Role of methylmercury exposure (from fish consumption) on growth and neurodevelopment of children under 5 years of age living in a transitioning (tin-mining) area of the western Amazon, Brazil. Arch Environ Contam Toxicol. 2012;62(2):341-50. | Study design, Independent variable
1464 | Marques, R. F.,Taddei, J. A.,Lopez, F. A.,Braga, J. A. Breastfeeding exclusively and iron deficiency anemia during the first 6 months of age. Rev Assoc Med Bras. 2014;60(1):18-22. | Independent variable
1465 | Marquis, G. S.,Habicht, J. P. Breastfeeding and stunting among toddlers in Peru. Adv Exp Med Biol. 2000;478:163-72. | Peer review
1466 | Marquis, G. S.,Habicht, J. P.,Lanata, C. F.,Black, R. E.,Rasmussen, K. M. Association of breastfeeding and stunting in Peruvian toddlers: an example of reverse causality. Int J Epidemiol. 1997;26(2):349-56. | Independent variable
1467 | Marquis, G. S.,Habicht, J. P.,Lanata, C. F.,Black, R. E.,Rasmussen, K. M. Breast milk or animal-product foods improve linear growth of Peruvian toddlers consuming marginal diets. Am J Clin Nutr. 1997;66(5):1102-9. | Independent variable
1468 | Marriage, B. J.,Buck, R. H.,Goehring, K. C.,Oliver, J. S.,Williams, J. A. Infants Fed a Lower Calorie Formula With 2’FL Show Growth and 2’FL Uptake Like Breast-Fed Infants. J Pediatr Gastroenterol Nutr. 2015;61(6):649-58. | Included for systematic reviews not completed
1469 | Marshall, J. Infant feeding. 6. Formula feed. Pract Midwife. 2013;16(3):35-8. | Study design
1470 | Martens, P. J.,Romphf, L. Factors associated with newborn in-hospital weight loss: comparisons by feeding method, demographics, and birthing procedures. J Hum Lact. 2007;23(3):233-41, quiz 242-5. | Included for systematic reviews not completed
1471 | Martin, A. J.,Landau, L. I.,Phelan, P. D. Natural history of allergy in asthmatic children followed to adult life. Med J Aust. 1981;2(9):470-4. | Study design, Independent variable
1472 | Martin, R. M.,Ben-Shlomo, Y.,Gunnell, D.,Elwood, P.,Yarnell, J. W.,Davey Smith, G. Breast feeding and cardiovascular disease risk factors, incidence, and mortality: the Caerphilly study. J Epidemiol Community Health. 2005;59(2):121-9. | Study design
1473 | Martin, R. M.,Ebrahim, S.,Griffin, M.,Davey Smith, G.,Nicolaides, A. N.,Georgiou, N.,Watson, S.,Frankel, S.,Holly, J. M.,Gunnell, D. Breastfeeding and atherosclerosis: intima-media thickness and plaques at 65-year follow-up of the Boyd Orr cohort. Arterioscler Thromb Vasc Biol. 2005;25(7):1482-8. | Independent variable
1474 | Martin, R. M.,Gunnell, D.,Pemberton, J.,Frankel, S.,Smith, G. D. Cohort profile: The Boyd Orr cohort - An historical cohort study based on the 65 year follow-up of the Carnegie Survey of Diet and Health (1937-39). International Journal of Epidemiology. 2005;34(4):742-749. | Study design
1475 | Martin, R. M.,Patel, R.,Kramer, M. S.,Guthrie, L.,Vilchuck, K.,Bogdanovich, N.,Sergeichick, N.,Gusina, N.,Foo, Y.,Palmer, T.,Rifas-Shiman, S. L.,Gillman, M. W.,Smith, G. D.,Oken, E. Effects of promoting longer-term and exclusive breastfeeding on adiposity and insulin-like growth factor-I at age 11.5 years: a randomized trial. JAMA. 2013;309(10):1005-13. | Included for systematic reviews not completed
1476 | Martin, R. M.,Smith, G. D.,Mangtani, P.,Frankel, S.,Gunnell, D. Association between breast feeding and growth: the Boyd-Orr cohort study. Arch Dis Child Fetal Neonatal Ed. 2002;87(3):F193-201. | Study design
1477 | Martines, F.,Bentivegna, D.,Maira, E.,Sciacca, V.,Martines, E. Risk factors for otitis media with effusion: case-control study in Sicilian schoolchildren. Int J Pediatr Otorhinolaryngol. 2011;75(6):754-9. | Study design
1478 | Martines, F.,Salvago, P.,Ferrara, S.,Messina, G.,Mucia, M.,Plescia, F.,Sireci, F. Factors influencing the development of otitis media among Sicilian children affected by upper respiratory tract infections. Brazilian Journal of Otorhinolaryngology. 2015. | Included for systematic reviews not completed
1479 | Martines, J. C.,Ashworth, A.,Kirkwood, B. Breast-feeding among the urban poor in southern Brazil: reasons for termination in the first 6 months of life. Bull World Health Organ. 1989;67(2):151-61. | Dependent variable
1480 | Martines, J. C.,Habicht, J. P.,Ashworth, A.,Kirkwood, B. R. Weaning in southern Brazil: is there a “weanling’s dilemma”?. J Nutr. 1994;124(8):1189-98. | Independent variable
1481 | Martorell, A.,Plaza, A. M.,Boné, J.,Nevot, S.,García Ara Ma, C.,Echeverria, L.,Alonso, E.,Garde, J.,Vila, B.,Alvaro, M.,Tauler, E.,Hernando, V.,Fernández, M. Cow’s milk protein allergy. A multi-centre study: Clinical and epidemiological aspects. Allergologia et Immunopathologia. 2006;34(2):46-53. | Study design, Independent variable
1482 | Martorell, R.,O’Gara, C. Breastfeeding, infant health, and socioeconomic status. Med Anthropol. 1985;9(2):173-81. | Country
1483 | Mason, J. K.,Harkness, R. A.,Elton, R. A.,Bartholomew, S. Cot deaths in Edinburgh: infant feeding and socioeconomic factors. J Epidemiol Community Health. 1980;34(1):35-41. | Study design, Independent variable
1484 | Massoni, A. C.,Chaves, A. M.,Rosenblatt, A.,Sampaio, F. C.,Oliveira, A. F. Prevalence of enamel defects related to pre-, peri- and postnatal factors in a Brazilian population. Community Dent Health. 2009;26(3):143-9. | Study design
1485 | Mata, L. Cryptosporidium and other protozoa in diarrheal disease in less developed countries. Pediatr Infect Dis. 1986;5(1 Suppl):S117-30. | Study design
1486 | Mata, L. Epidemiologic perspective of diarrheal disease in Costa Rica and current efforts in control, prevention, and research. Rev Latinoam Microbiol. 1981;23(2):109-19. | Study design
1487 | Mata, L.,Bolanos, H.,Pizarro, D.,Vives, M. Cryptosporidiosis in children from some highland Costa Rican rural and urban areas. Am J Trop Med Hyg. 1984;33(1):24-9. | Study design, Independent variable
1488 | Matee MI,Mikx FH,Maselle SY,Van Palenstein Helderman WH. Rampant caries and linear hypoplasia (short communication). Caries Res. 1992;26:205-8. | Country
1489 | Matheson, M. C.,Erbas, B.,Balasuriya, A.,Jenkins, M. A.,Wharton, C. L.,Tang, M. L.,Abramson, M. J.,Walters, E. H.,Hopper, J. L.,Dharmage, S. C. Breast-feeding and atopic disease: a cohort study from childhood to middle age. J Allergy Clin Immunol. 2007;120(5):1051-7. | Independent variable
1490 | Matsuda, I.,Higashi, A.,Ikeda, T.,Uehara, I.,Kuroki, Y. Effects of zinc and copper content of formulas on growth and on the concentration of zinc and copper in serum and hair. J Pediatr Gastroenterol Nutr. 1984;3(3):421-5. | Group size
1491 | Matthews, M. K.,Webber, K.,McKim, E.,Banoub-Baddour, S.,Laryea, M. Infant feeding practices in Newfoundland and Labrador. Can J Public Health. 1995;86(5):296-300. | Dependent variable
1492 | Mattos-Graner, R. O.,Zelante, F.,Line, R. C.,Mayer, M. P. Association between caries prevalence and clinical, microbiological and dietary variables in 1.0 to 2.5-year-old Brazilian children. Caries Res. 1998;32(5):319-23. | Study design
1493 | Maupome, G.,Karanja, N.,Ritenbaugh, C.,Lutz, T.,Aickin, M.,Becker, T. Dental caries in American Indian toddlers after a community-based beverage intervention. Ethn Dis. 2010;20(4):444-50. | Independent variable
1494 | May, R.,Barber, J.,Simpson, T.,Winders, N.,Kuhler, K.,Schroeder, S. Growth pattern of overweight preschool children in the Siouxland WIC program. Am J Hum Biol. 2002;14(6):769-76. | Health status
1495 | May, R.,Kim, D.,Mote-Watson, D. Change in weight-for-length status during the first three months: relationships to birth weight and implications for metabolic risk. Am J Phys Anthropol. 2013;150(1):5-9. | Study design
1496 | Mayer-Davis, E. J.,Dabelea, D.,Crandell, J. L.,Crume, T.,D’Agostino, R. B., Jr.,Dolan, L.,King, I. B.,Lawrence, J. M.,Norris, J. M.,Pihoker, C.,The, N. Nutritional factors and preservation of C-peptide in youth with recently diagnosed type 1 diabetes: SEARCH Nutrition Ancillary Study. Diabetes Care. 2013;36(7):1842-50. | Study design, Dependent variable, Health status
1497 | Mayer-Davis, E. J.,Rifas-Shiman, S. L.,Zhou, L.,Hu, F. B.,Colditz, G. A.,Gillman, M. W. Breast-feeding and risk for childhood obesity: does maternal diabetes or obesity status matter?. Diabetes Care. 2006;29(10):2231-7. | Study design
1498 | McAllister, J. C.,Lane, A. T.,Buckingham, B. A. Vitamin D deficiency in the San Francisco Bay Area. J Pediatr Endocrinol Metab. 2006;19(3):205-8. | Study design
1499 | McCann, M. F.,Moggia, A. V.,Higgins, J. E.,Potts, M.,Becker, C. The effects of a progestin-only oral contraceptive (levonorgestrel 0.03 mg) on breast-feeding. Contraception. 1989;40(6):635-48. | Independent variable
1500 | McConnochie, K. M.,Roghmann, K. J. Breast feeding and maternal smoking as predictors of wheezing in children age 6 to 10 years. Pediatr Pulmonol. 1986;2(5):260-8. | Independent variable
1501 | McCormick, D. P.,Grady, J. J.,Diego, A.,Matalon, R.,Revai, K.,Patel, J. A.,Han, Y.,Chonmaitree, T. Acute otitis media severity: association with cytokine gene polymorphisms and other risk factors. Int J Pediatr Otorhinolaryngol. 2011;75(5):708-12. | Dependent variable
1502 | McCrory, C.,Layte, R. Breastfeeding and risk of overweight and obesity at nine-years of age. Soc Sci Med. 2012;75(2):323-30. | Included for systematic reviews not completed
1503 | McCrory, C.,Murray, A. The effect of breastfeeding on neuro-development in infancy. Matern Child Health J. 2013;17(9):1680-8. | Study design
1504 | McCusker, C. Teaching tolerance: Using the neonatal immune system to prevent allergic asthma. Expert Review of Clinical Immunology. 2008;4(4):429-432. | Study design
1505 | McDougall, P.,Drewett, R. F.,Hungin, A. P. S.,Wright, C. M. The detection of early weight faltering at the 6-8-week check and its association with family factors, feeding and behavioural development. Archives of Disease in Childhood. 2009;94(7):549-552. | Included for systematic reviews not completed
1506 | McEnery, G.,Rao, K. P. The effectiveness of antenatal education of Pakistani and Indian women living in this country. Child Care Health Dev. 1986;12(6):385-99. | Independent variable
1507 | McIntosh, E. D.,De Silva, L. M.,Oates, R. K. Clinical severity of respiratory syncytial virus group A and B infection in Sydney, Australia. Pediatr Infect Dis J. 1993;12(10):815-9. | Health status
1508 | McIsaac, K. E.,Moineddin, R.,Matheson, F. I. Breastfeeding as a means to prevent infant morbidity and mortality in Aboriginal Canadians: A population prevented fraction analysis. Can J Public Health. 2015;106(4):e217-22. | Study design
1509 | McKinney, P. A.,Parslow, R.,Gurney, K. A.,Law, G. R.,Bodansky, H. J.,Williams, R. Perinatal and neonatal determinants of childhood type 1 diabetes. A case-control study in Yorkshire, U.K. Diabetes Care. 1999;22(6):928-32. | Independent variable
1510 | McMichael, A. J. Widening the horizons of ‘evidence’: Nutrition and disease in ecological perspective. South African Journal of Clinical Nutrition. 2005;18(2):140-148. | Study design
1511 | McNamara, T. M.,Melnyk, B. M. The effect of food intake on atopic disease in high-risk infants and young children. Pediatric nursing. 2000;26(6):602-604. | Study design
1512 | McTeer, H. Fat, young, and poor: why breastfeeding is a critical weapon in the fight against childhood obesity. Breastfeed Med. 2012;7(5):325-6. | Study design
1513 | Meador, K. J.,Baker, G. A.,Browning, N.,Clayton-Smith, J.,Combs-Cantrell, D. T.,Cohen, M.,Kalayjian, L. A.,Kanner, A.,Liporace, J. D.,Pennell, P. B.,Privitera, M.,Loring, D. W. Effects of breastfeeding in children of women taking antiepileptic drugs. Neurology. 2010;75(22):1954-60. | Independent variable
1514 | Meador, K. J.,Baker, G. A.,Browning, N.,Cohen, M. J.,Bromley, R. L.,Clayton-Smith, J.,Kalayjian, L. A.,Kanner, A.,Liporace, J. D.,Pennell, P. B.,Privitera, M.,Loring, D. W. Breastfeeding in children of women taking antiepileptic drugs: cognitive outcomes at age 6 years. JAMA Pediatr. 2014;168(8):729-36. | Included for systematic reviews not completed
1515 | Meah, S. A breastfeeding intervention increased breast feeding and reduced GI tract infections and atopic eczema. Evidence Based Nursing. 2001:106-106 1p. | Study design
1516 | Megeid, F. Y. A.,Bakeit, Z. A. N.,Karim, B. O. I. A. A. Early introduction of cow’s milk and short duration of breastfeeding is associated with increasing risk of juvenile diabetes. World Journal of Medical Sciences. 2011;6(2):54-60. | Study design
1517 | Megraud, F.,Boudraa, G.,Bessaoud, K.,Bensid, S.,Dabis, F.,Soltana, R.,Touhami, M. Incidence of Campylobacter infection in infants in western Algeria and the possible protective role of breast feeding. Epidemiol Infect. 1990;105(1):73-8. | Study design
1518 | Meinzen-Derr, J. K.,Guerrero, M. L.,Altaye, M.,Ortega-Gallegos, H.,Ruiz-Palacios, G. M.,Morrow, A. L. Risk of infant anemia is associated with exclusive breast-feeding and maternal anemia in a Mexican cohort. J Nutr. 2006;136(2):452-8. | Independent variable
1519 | Meinzen-Derr, J. K.,Guerrero, M. L.,Altaye, M.,Ruiz-Palacios, G. M.,Morrow, A. L. Duration of exclusive breastfeeding and risk of anemia in a cohort of Mexican infants. Adv Exp Med Biol. 2004;554:395-8. | Peer review
1520 | Mellander, M.,Noren, J. G.,Freden, H.,Kjellmer, I. Mineralization defects in deciduous teeth of low birthweight infants. Acta Paediatr Scand. 1982;71(5):727-33. | Independent variable, Health status
1521 | Melville B. The high cost of artificial feeding in Jamaica and its implications for child health. West Indian Med J. 1990;39:203-4. | Study design
1522 | Mendelson, M.,Cloutier, J.,Spence, L.,Sellers, E.,Taback, S.,Dean, H. Obesity and type 2 diabetes mellitus in a birth cohort of First Nation children born to mothers with pediatric-onset type 2 diabetes. Pediatr Diabetes. 2011;12(3 Pt 2):219-28. | Independent variable
1523 | Mendez, M. A.,Torrent, M.,Julvez, J.,Ribas-Fito, N.,Kogevinas, M.,Sunyer, J. Maternal fish and other seafood intakes during pregnancy and child neurodevelopment at age 4 years. Public Health Nutr. 2009;12(10):1702-10. | Included for systematic reviews not completed
1524 | Menihan, C. A.,Phipps, M.,Weitzen, S. Fetal heart rate patterns and sudden infant death syndrome. J Obstet Gynecol Neonatal Nurs. 2006;35(1):116-22. | Independent variable
1525 | Merlob, P.,Aloni, R.,Prager, H.,Jelin, N.,Idel, M.,Kotona, J. Continued weight loss in the newborn during the third day of life as an indicator of early weaning. Israel Journal of Medical Sciences. 1994;30(8):646-648. | Independent variable, Dependent variable
1526 | Merlob, P.,Stahl, B.,Sulkes, J. Paroxetine during breast-feeding: infant weight gain and maternal adherence to counsel. Eur J Pediatr. 2004;163(3):135-9. | Included for systematic reviews not completed
1527 | Merrett, T. G.,Burr, M. L.,Butland, B. K.,Merrett, J.,Miskelly, F. G.,Vaughan Williams, E. Infant feeding and allergy: 12-month prospective study of 500 babies born into allergic families. Review 53 refs. Annals of allergy. 1988;61(6 (Pt 2)):13-20. | Redundant data
1528 | Metcalfe, D. D. Food hypersensitivity. J Allergy Clin Immunol. 1984;73(6):749-62. | Study design, Independent variable
1529 | Metzger, M. W.,McDade, T. W. Breastfeeding as obesity prevention in the United States: a sibling difference model. Am J Hum Biol. 2010;22(3):291-6. | Included for systematic reviews not completed
1530 | Meyers, A.,Hertzberg, J. Bottle-feeding and malocclusion: is there an association?. Am J Orthod Dentofacial Orthop. 1988;93(2):149-52. | Study design
1531 | Micali, N.,Simonoff, E.,Treasure, J. Infant feeding and weight in the first year of life in babies of women with eating disorders. J Pediatr. 2009;154(1):55-60 e1. | Included for systematic reviews not completed
1532 | Michaelsen KF. 1.1 Child growth. World Rev Nutr Diet. 2015;113:1-5. | Peer review
1533 | Michaelsen, K. F. 2.1 Breastfeeding. World Rev Nutr Diet. 2015;113:92-6. | Study design
1534 | Michaelsen, K. F. Nutrition and growth during infancy. The Copenhagen Cohort Study. Acta Paediatr Suppl. 1997;420:1-36. | Included for systematic reviews not completed
1535 | Michaelsen, K. F.,Larnkjaer, A.,Molgaard, C. Early diet, insulin-like growth factor-1, growth and later obesity. World Rev. Nutr. Diet. 2013;106:113-118. | Peer review
1536 | Michaelsen, K. F.,Petersen, S.,Greisen, G.,Thomsen, B. L. Weight, length, head circumference, and growth velocity in a longitudinal study of Danish infants. Dan Med Bull. 1994;41(5):577-85. | Study design, Independent variable
1537 | Michels, K. B.,Willett, W. C.,Graubard, B. I.,Vaidya, R. L.,Cantwell, M. M.,Sansbury, L. B.,Forman, M. R. A longitudinal study of infant feeding and obesity throughout life course. Int J Obes (Lond). 2007;31(7):1078-85. | Included for systematic reviews not completed
1538 | Michie, C. A.,Gilmour, J. Breast feeding and the risks of viral transmission. Arch Dis Child. 2001;84(5):381-2. | Study design
1539 | Michie, C. Breast feeding could reduce the risk of childhood leukaemias. Evid Based Nurs. 2016. | Study design
1540 | Midodzi, W. K.,Rowe, B. H.,Majaesic, C. M.,Saunders, L. D.,Senthilselvan, A. Predictors for wheezing phenotypes in the first decade of life. Respirology. 2008;13(4):537-45. | Dependent variable
1541 | Midwinter, R. E.,Morris, A. F.,Colley, J. R. Infant feeding and atopy. Arch Dis Child. 1987;62(9):965-7. | Study design, Independent variable
1542 | Mihrshahi, S.,Battistutta, D.,Magarey, A.,Daniels, L. A. Determinants of rapid weight gain during infancy: baseline results from the NOURISH randomised controlled trial. BMC Pediatr. 2011;11:99. | Included for systematic reviews not completed
1543 | Mikiel-Kostyra, K.,Mazur, J. Hospital policies and their influence on newborn body weight. Acta Paediatr. 1999;88(1):72-5. | Study design, Independent variable
1544 | Milaat, W. A.,Elassouli, S. M. Epidemiology of diarrhoea in two major cities in Saudi Arabia. J Commun Dis. 1995;27(2):84-91. | Study design, Health status
1545 | Milankov, O.,Bjelica, M.,Savic, R. What kind of milk can prevent infant’s sideropenic anemia--comparative study. Med Pregl. 2014;67(5-6):167-71. | Study design, Health status
1546 | Miliku, K.,Voortman, T.,Bakker, H.,Hofman, A.,Franco, O. H.,Jaddoe, V. W. Infant Breastfeeding and Kidney Function in School-Aged Children. Am J Kidney Dis. 2015;66(3):421-8. | Dependent variable
1547 | Miljanovic, O.,Cikota-Aleksic, B.,Likic, D.,Vojvodic, D.,Jovicevic, O.,Magic, Z. Association of cytokine gene polymorphisms and risk factors with otitis media proneness in children. Eur J Pediatr. 2016. | Included for systematic reviews not completed
1548 | Millard, A. V.,Graham, M. A. Abrupt weaning reconsidered: evidence from central Mexico. J Trop Pediatr. 1985;31(4):229-34. | Study design, Dependent variable
1549 | Mills, A. F. Surveillance for anaemia: risk factors in patterns of milk intake. Arch Dis Child. 1990;65(4):428-31. | Study design
1550 | Mills, R. P. Persistent middle ear effusions in children with recurrent acute otitis media. Clin Otolaryngol Allied Sci. 1987;12(2):97-101. | Health status
1551 | Milnes, A. R.,Bowden, G. H. The microflora associated with developing lesions of nursing caries. Caries Res. 1985;19(4):289-97. | Group size
1552 | Mimouni-Bloch, A.,Kachevanskaya, A.,Mimouni, F. B.,Shuper, A.,Raveh, E.,Linder, N. Breastfeeding may protect from developing attention-deficit/hyperactivity disorder. Breastfeed Med. 2013;8(4):363-7. | Included for systematic reviews not completed
1553 | Minchin, M. Artificial feeding and risk. Pract Midwife. 2000;3(3):18-20. | Study design
1554 | Minchin, M. Infant formula: a mass, uncontrolled trial in perinatal care. Birth. 1987;14(1):25-35. | Study design
1555 | Mindru, D. E.,Moraru, E. Risk factors and their implications in the epidemiology of pediatric obesity. Rev Med Chir Soc Med Nat Iasi. 2012;116(3):739-45. | Study design
1556 | Miranda, B. H.,Milroy, C. J. A quick snip - A study of the impact of outpatient tongue tie release on neonatal growth and breastfeeding. J Plast Reconstr Aesthet Surg. 2010;63(9):e683-5. | Independent variable
1557 | Misra, S.,Sabui, T. K.,Basu, S.,Pal, N. A prospective study of rotavirus diarrhea in children under 1 year of age. Clin Pediatr (Phila). 2007;46(8):683-8. | Country
1558 | Mitchell, E. A.,Blair, P. S. SIDS prevention: 3000 lives saved but we can do better. N Z Med J. 2012;125(1359):50-7. | Study design
1559 | Mitchell, E. A.,Esmail, A.,Jones, D. R.,Clements, M. Do differences in the prevalence of risk factors explain the higher mortality from sudden infant death syndrome in New Zealand compared with the UK?. N Z Med J. 1996;109(1030):352-5. | Study design
1560 | Mitchell, E. A.,Scragg, R.,Stewart, A. W.,Becroft, D. M.,Taylor, B. J.,Ford, R. P.,Hassall, I. B.,Barry, D. M.,Allen, E. M.,Roberts, A. P. Results from the first year of the New Zealand cot death study. N Z Med J. 1991;104(906):71-6. | Included for systematic reviews not completed
1561 | Mitchell, E. A.,Stewart, A. W.,Scragg, R.,Ford, R. P.,Taylor, B. J.,Becroft, D. M.,Thompson, J. M.,Hassall, I. B.,Barry, D. M.,Allen, E. M.,et al.,. Ethnic differences in mortality from sudden infant death syndrome in New Zealand. BMJ. 1993;306(6869):13-6. | Study design, Independent variable
1562 | Mitchell, E. A.,Thompson, J. M. Parental reported apnoea, admissions to hospital and sudden infant death syndrome. Acta Paediatr. 2001;90(4):417-22. | Study design, Independent variable
1563 | Mitchell, E. A.,Tuohy, P. G.,Brunt, J. M.,Thompson, J. M.,Clements, M. S.,Stewart, A. W.,Ford, R. P.,Taylor, B. J. Risk factors for sudden infant death syndrome following the prevention campaign in New Zealand: a prospective study. Pediatrics. 1997;100(5):835-40. | Included for systematic reviews not completed
1564 | Mittal, S. K. Bowel pattern and weight gain in breast fed infants. Indian Pediatr. 1988;25(2):216-7. | Study design
1565 | Mittal, S. K.,Kanwar, A.,Varghese, A.,Ramachandran, V. G. Gut flora in breast and bottle fed infants with and without diarrhea. Indian Pediatr. 1983;20(1):21-6. | Country
1566 | Miyake, Y.,Tanaka, K.,Sasaki, S.,Kiyohara, C.,Ohya, Y.,Fukushima, W.,Yokoyama, T.,Hirota, Y. Breastfeeding and the risk of wheeze and asthma in Japanese infants: the Osaka Maternal and Child Health Study. Pediatr Allergy Immunol. 2008;19(6):490-6. | Study design
1567 | Miyamoto, S.,Murotani, K.,Yanagawa, T.,Kato, A.,Matsunaga, S. Relationship of low lean body mass with body weight increase until one year of age and current lifestyles in Japanese young women. J Hum Ergol (Tokyo). 2010;39(1):45-51. | Study design, Independent variable
1568 | Mize, C. E.,Uauy, R.,Kramer, R.,Benser, M.,Allen, S.,Grundy, S. M.. Lipoprotein-cholesterol responses in healthy infants fed defined diets from ages 1 to 12 months: comparison of diets predominant in oleic acid versus linoleic acid, with parallel observations in infants fed a human milk-based diet. J Lipid Res. 1995;36(6):1178-87. | Included for systematic reviews not completed
1569 | Mizuno, K.,Ueda, A.,Takeuchi, T. Effects of different fluids on the relationship between swallowing and breathing during nutritive sucking in neonates. Biol Neonate. 2002;81(1):45-50. | Study design
1570 | Modi, N.,Thomas, E. L.,Harrington, T. A.,Uthaya, S.,Dore, C. J.,Bell, J. D. Determinants of adiposity during preweaning postnatal growth in appropriately grown and growth-restricted term infants. Pediatr Res. 2006;60(3):345-8. | Group size
1571 | Moimaz, S. A.,Garbin, A. J.,Lima, A. M.,Lolli, L. F.,Saliba, O.,Garbin, C. A. Longitudinal study of habits leading to malocclusion development in childhood. BMC Oral Health. 2014;14:96. | Included for systematic reviews not completed
1572 | Mok, J. Y.,Simpson, H. Outcome of acute lower respiratory tract infection in infants: preliminary report of seven-year follow-up study. Br Med J (Clin Res Ed). 1982;285(6338):333-7. | Study design
1573 | Molgaard, C.,Larnkjaer, A.,Mark, A. B.,Michaelsen, K. F. Are early growth and nutrition related to bone health in adolescence? The Copenhagen Cohort Study of infant nutrition and growth. Am J Clin Nutr. 2011;94(6 Suppl):1865S-1869S. | Included for systematic reviews not completed
1574 | Molla, A. M.,Badawi, M. H.,Al-Yaish, S.,Sharma, P.,El-Salam, R. S.,Molla, A. M. Risk factors for nutritional rickets among children in Kuwait. Pediatrics International. 2000;42(3):280-284. | Independent variable
1575 | Mollborg, P.,Wennergren, G.,Almqvist, P.,Alm, B. Bed sharing is more common in sudden infant death syndrome than in explained sudden unexpected deaths in infancy. Acta Paediatr. 2015;104(8):777-83. | Dependent variable
1576 | Molokhia, E. A.,Perkins, A. Preventing cancer. Prim Care. 2008;35(4):609-23. | Study design
1577 | Monobe, H.,Ishibashi, T.,Fujishiro, Y.,Shinogami, M.,Yano, J. Factors associated with poor outcome in children with acute otitis media. Acta Otolaryngol. 2003;123(5):564-8. | Study design
1578 | Monson, T. P. Pediatric viral gastroenteritis. Am Fam Physician. 1986;34(1):95-9. | Study design
1579 | Montagu, A. The skin, touch, and human development. Clin Dermatol. 1984;2(4):17-26. | Study design
1580 | Monte, W. C.,Johnston, C. S.,Roll, L. E. Bovine serum albumin detected in infant formula is a possible trigger for insulin-dependent diabetes mellitus. J Am Diet Assoc. 1994;94(3):314-6. | Study design, Non-human
1581 | Montefort, S.,Muscat, H. A.,Caruana, S.,Lenicker, H. Allergic conditions in 5-8-year-old Maltese schoolchildren: prevalence, severity, and associated risk factors [ISAAC]. Pediatr Allergy Immunol. 2002;13(2):98-104. | Study design
1582 | Monterrosa, E. C.,Frongillo, E. A.,Vasquez-Garibay, E. M.,Romero-Velarde, E.,Casey, L. M.,Willows, N. D. Predominant breast-feeding from birth to six months is associated with fewer gastrointestinal infections and increased risk for iron deficiency among infants. J Nutr. 2008;138(8):1499-504. | Included for systematic reviews not completed
1583 | Montgomery, S. M.,Ehlin, A.,Sacker, A. Breast feeding and resilience against psychosocial stress. Arch Dis Child. 2006;91(12):990-4. | Included for systematic reviews not completed
1584 | Moon, R. Y.,Tanabe, K. O.,Yang, D. C.,Young, H. A.,Hauck, F. R. Pacifier use and SIDS: evidence for a consistently reduced risk. Maternal and child health journal. 2012;16(3):609-614. | Included for systematic reviews not completed
1585 | Moore, Elizabeth R. Early Skin-To-Skin Contact for Mothers and Their Healthy Newborn Infants. JOGNN: Journal of Obstetric, Gynecologic & Neonatal Nursing. 2013;42:S86-S86 1p. | Study design
1586 | Moore, S. R.,Lima, N. L.,Soares, A. M.,Oria, R. B.,Pinkerton, R. C.,Barrett, L. J.,Guerrant, R. L.,Lima, A. A. Prolonged episodes of acute diarrhea reduce growth and increase risk of persistent diarrhea in children. Gastroenterology. 2010;139(4):1156-64. | Included for systematic reviews not completed
1587 | Moore, W. J.,Midwinter, R. E.,Morris, A. F.,Colley, J. R.,Soothill, J. F. Infant feeding and subsequent risk of atopic eczema. Arch Dis Child. 1985;60(8):722-6. | Independent variable
1588 | Mora Urda, A. I.,Pereira da Silva, R.,Bisi Molina Mdel, C.,Bresciani Salaroli, L.,Montero Lopez Mdel, P. [RELATIONSHIP BETWEEN PATTERNS OF BREASTFEEDING AND BLOOD PRESSURE IN BRAZILIAN AND SPANISH SCHOOLCHILDREN]. Nutr Hosp. 2015;32(4):1568-75. | Language
1589 | Moraeus, L.,Lissner, L.,Yngve, A.,Poortvliet, E.,Al-Ansari, U.,Sjoberg, A. Multi-level influences on childhood obesity in Sweden: societal factors, parental determinants and child’s lifestyle. Int J Obes (Lond). 2012;36(7):969-76. | Study design, Independent variable
1590 | Morales, E.,Bustamante, M.,Gonzalez, J. R.,Guxens, M.,Torrent, M.,Mendez, M.,Garcia-Esteban, R.,Julvez, J.,Forns, J.,Vrijheid, M.,Molto-Puigmarti, C.,Lopez-Sabater, C.,Estivill, X.,Sunyer, J. Genetic variants of the FADS gene cluster and ELOVL gene family, colostrums LC-PUFA levels, breastfeeding, and child cognition. PLoS One. 2011;6(2):e17181. | Group size
1591 | Moran, J. R. Effects of prolonged exposure to partially hydrolyzed milk protein. J Pediatr. 1992;121(5 Pt 2):S90-4. | Included for systematic reviews not completed
1592 | Moreno, M. Early infant feeding and obesity risk. JAMA Pediatr. 2014;168(11):1084. | Study design
1593 | Morgan, J. B.,Mumford, P. M. A follow-up study of nutrition and anthropometry in pre-school children. Proc Nutr Soc. 1980;39(1):5A. | Peer review
1594 | Morgan, J.,Taylor, A.,Fewtrell, M. Meat consumption is positively associated with psychomotor outcome in children up to 24 months of age. J Pediatr Gastroenterol Nutr. 2004;39(5):493-8. | Included for systematic reviews not completed
1595 | Morin, K. H. Breastfeeding immediately after birth. MCN Am J Matern Child Nurs. 2009;34(1):63. | Study design
1596 | Morley, R. Iron supplemented follow-on formula and growth and development: a randomised trial [abstract]. Proc Nutr Soc Aust. 1998;22:288. | Peer review
1597 | Morley-Peet, P. Enteropathogenic Escherichia coli. Nurs Times. 1983;79(23):24-7. | Study design
1598 | Moro, D. Birthweight and breast feeding of babies born during the war in one municipal area of Sarajevo. Eur J Clin Nutr. 1995;49 Suppl 2:S37-9. | Independent variable, Dependent variable
1599 | Morris, S. S.,Grantham-McGregor, S. M.,Lira, P. I.,Assuncao, A. M.,Ashworth, A. Effect of breastfeeding and morbidity on the development of low birthweight term babies in Brazil. Acta Paediatr. 1999;88(10):1101-6. | Independent variable
1600 | Morrow, A. L. Infant feeding in the 21st century. J Pediatr Health Care. 2011;25(3):195-7. | Study design, Dependent variable
1601 | Morrow, A. L.,Guerrero, M. L. From bioactive substances to research on breast-feeding promotion. Adv Exp Med Biol. 2001;501:447-55. | Study design, Independent variable
1602 | Morrow, A. L.,Reves, R. R.,West, M. S.,Guerrero, M. L.,Ruiz-Palacios, G. M.,Pickering, L. K. Protection against infection with Giardia lamblia by breast-feeding in a cohort of Mexican infants. J Pediatr. 1992;121(3):363-70. | Independent variable
1603 | Morrow-Tlucak, M.,Haude, R. H.,Ernhart, C. B. Breastfeeding and cognitive development in the first 2 years of life. Soc Sci Med. 1988;26(6):635-9. | Included for systematic reviews not completed
1604 | Mortensen, E. L.,Michaelsen, K. F.,Sanders, S. A.,Reinisch, J. M. The association between duration of breastfeeding and adult intelligence. JAMA. 2002;287(18):2365-71. | Included for systematic reviews not completed
1605 | Moschonis, G.,Grammatikaki, E.,Manios, Y. Perinatal predictors of overweight at infancy and preschool childhood: the GENESIS study. Int J Obes (Lond). 2008;32(1):39-47. | Study design
1606 | Moss, B. G.,Yeaton, W. H. Early childhood healthy and obese weight status: potentially protective benefits of breastfeeding and delaying solid foods. Matern Child Health J. 2014;18(5):1224-32. | Included for systematic reviews not completed
1607 | Mo-Suwan, L.,Junjana, C. Breast-feeding and infant growth in the first six months. J Med Assoc Thai. 1991;74(9):386-90. | Independent variable
1608 | Motil, K. J.,Sheng, H. P.,Montandon, C. M.,Wong, W. W. Human milk protein does not limit growth of breast-fed infants. J Pediatr Gastroenterol Nutr. 1997;24(1):10-7. | Group size
1609 | Motta, M.,Tincani, A.,Faden, D.,Zinzini, E.,Lojacono, A.,Marchesi, A.,Frassi, M.,Biasini, C.,Zatti, S.,Chirico, G. Follow-up of infants exposed to hydroxychloroquine given to mothers during pregnancy and lactation. J Perinatol. 2005;25(2):86-9. | Group size
1610 | Moxley, S.,Avni, G.,Brydon, S.,Kennedy, M. Breastfeeding and shorter hospital stays. Can Nurse. 1998;94(7):35-9. | Study design
1611 | Mueller, W. H.,Pollitt, E. The Bacon Chow study: effects of nutrition supplementation on sibling-sibling anthropometric correlations. Hum Biol. 1982;54(3):455-68. | Study design, Independent variable
1612 | Mughal, M. Z.,Salama, H.,Greenaway, T.,Laing, I.,Mawer, E. B. Lesson of the week: florid rickets associated with prolonged breast feeding without vitamin D supplementation. Bmj. 1999;318(7175):39-40. | Study design
1613 | Mughini-Gras, L.,Pijnacker, R.,Heusinkveld, M.,Enserink, R.,Zuidema, R.,Duizer, E.,Kortbeek, T.,van Pelt, W. Societal Burden and Correlates of Acute Gastroenteritis in Families with Preschool Children. Sci Rep. 2016;6:22144. | Study design
1614 | Muiño, A.,Menezes, A. M. B.,Reichert, F. F.,Duquia, R. P.,Chatkin, M. Wheezing phenotypes from birth to adolescence: A cohort study in Pelotas, Brazil, 1993-2004. Jornal Brasileiro de Pneumologia. 2008;34(6):347-355. | Dependent variable
1615 | Muirhead, P. A randomized controlled study of the effect of organised peer support on the duration of breast feeding and the consequences for infant morbidity. Personal communication. 1998. | Study design
1616 | Mukherjee, D.,Stephens, D. Otitis media with effusion in intellectually disabled children. Journal of Audiological Medicine. 1997;6(1):10-23. | Study design, Independent variable
1617 | Mukhopadhya, J. Acute Respiratory Infection among children in an Air Force Community. Medical Journal Armed Forces India. 2001;57(4):309-311. | Country
1618 | Mukhopadhyay, S.,Lieberman, E. S.,Puopolo, K. M.,Riley, L. E.,Johnson, L. C. Effect of early-onset sepsis evaluations on in-hospital breastfeeding practices among asymptomatic term neonates. Hosp Pediatr. 2015;5(4):203-10. | Dependent variable
1619 | Mulhall AL. Breast feeding: a challenge for midwives. World Ir Nurs. 1984;13:8-9. | No full text
1620 | Muller, M. Nursing-bottle syndrome: risk factors. ASDC J Dent Child. 1996;63(1):42-50. | Study design
1621 | Munir M,Mustadjab I,Rampengan TH,Wulur FH. Problem of infant feeding practices: implications for immediate action. Paediatr Indones. 1983;23:32-46. | Country
1622 | Munir, M. Infantile diarrhoea: breast and bottle feeding compared with special reference to their clinical role. Paediatr Indones. 1985;25(5-6):100-6. | Study design, Health status
1623 | Muniz, L. C.,Menezes, A. M.,Assuncao, M. C.,Wehrmeister, F. C.,Martinez-Mesa, J.,Goncalves, H.,Domingues, M. R.,Gigante, D. P.,Horta, B. L.,Barros, F. C. Breastfeeding and bone mass at the ages of 18 and 30: prospective analysis of live births from the Pelotas (Brazil) 1982 and 1993 cohorts. PLoS One. 2015;10(4):e0122759. | Included for systematic reviews not completed
1624 | Murdoch, W. Breast feeding. Cent Afr J Med. 1980;26(4):95-7. | Study design
1625 | Murphy RM. The hidden epidemic. Can Nurse. 1981;77:42-3. | Study design
1626 | Murrell, W. G.,Stewart, B. J.,O’Neill, C.,Siarakas, S.,Kariks, S. Enterotoxigenic bacteria in the sudden infant death syndrome. Journal of Medical Microbiology. 1993;39(2):114-127. | Independent variable
1627 | Musaad, S. M.,Donovan, S. M.,Fiese, B. H. Parental perception of child weight in the first two years-of-life: a potential link between infant feeding and preschoolers’ diet. Appetite. 2015;91:90-100. | Study design
1628 | Myres AW,Watson J,Harrison C. The national breast-feeding promotion program 1. Professional phase--a note on its development, distribution and impact. Can J Public Health. 1981;72:307-11. | Study design
1629 | Myres AW. The national breast-feeding promotion program. Part 2. Public information phase--a note on its development, distribution and impact. Can J Public Health. 1983;74:404-8. | Study design, Dependent variable
1630 | Myres, A. W. Tradition and technology in infant feeding--achieving the best of both worlds. Can J Public Health. 1988;79(2):78-80. | Study design
1631 | Nafstad, P.,Jaakkola, J. J.,Hagen, J. A.,Botten, G.,Kongerud, J. Breastfeeding, maternal smoking and lower respiratory tract infections. Eur Respir J. 1996;9(12):2623-9. | Included for systematic reviews not completed
1632 | Nafstad, P.,Jaakkola, J. J.,Hagen, J. A.,Pedersen, B. S.,Qvigstad, E.,Botten, G.,Kongerud, J. Weight gain during the first year of life in relation to maternal smoking and breast feeding in Norway. J Epidemiol Community Health. 1997;51(3):261-5. | Included for systematic reviews not completed
1633 | Nagahara, K.,Dobashi, K.,Itabashi, K. Feeding choice has a gender-associated effect on infant growth. Pediatr Int. 2013;55(4):481-7. | Included for systematic reviews not completed
1634 | Nagendra, R.,Viswanatha, S.,Arun Kumar, S.,Krishna Murthy, B.,Venkat Rao, S. Effect of feeding milk formula containing lactulose to infants on faecal bifidobacterial flora. Nutrition Research. 1995;15(1):15-24. | Group size
1635 | Naggan, L.,Forman, M. R.,Sarov, B.,Lewando-Hundt, G.,Zangwill, L.,Chang, D.,Berendes, H. W. The Bedouin Infant Feeding Study: study design and factors influencing the duration of breast feeding. Paediatr Perinat Epidemiol. 1991;5(4):428-44. | Dependent variable
1636 | Najada, A. S.,Habashneh, M. S.,Khader, M. The frequency of nutritional rickets among hospitalized infants and its relation to respiratory diseases. J Trop Pediatr. 2004;50(6):364-8. | Study design, Health status
1637 | Nakamura, Y.,Oki, I.,Tanihara, S.,Ojima, T.,Ito, Y.,Yamazaki, O.,Iwama, M.,Tabata, Y.,Katsuyama, K.,Sasai, Y.,Nakagawa, M.,Matsushita, A.,Hossaka, K.,Sato, J.,Hidaka, Y.,Uda, H.,Nakamata, K.,Yanagawa, H. Relationship between breast milk feeding and atopic dermatitis in children. J Epidemiol. 2000;10(2):74-8. | Study design
1638 | Nakao, R. M. Effects of an education program on the health and illness profile of rural breast-fed babies. Philipp J Nurs. 1988;58(2):12-8. | Country
1639 | Nambiar, H. K. Acute diarrhoeal diseases: a malady in children. Nurs J India. 1984;75(8):179. | Study design
1640 | Nambiar, Smita,Truby, Helen,Davies, Peter S. W. Exploring the influence of breastfeeding on abdominal adiposity in young children using the waist to height ratio. Nutrition & Dietetics. 2013;70(2):146-152 7p. | Study design
1641 | Narayan, N. R.,Mendez-Lagares, G.,Ardeshir, A.,Lu, D.,Van Rompay, K. K.,Hartigan-O’Connor, D. J. Persistent effects of early infant diet and associated microbiota on the juvenile immune system. Gut Microbes. 2015;6(4):284-9. | Non-human
1642 | Narayanan, I.,Gupta, J. Human milk and neonatal infections. Acta Paediatr Scand Suppl. 1989;351:126-30. | Dependent variable, Country
1643 | Narayanan, I.,Prakash, K.,Murthy, N. S.,Gujral, V. V. Randomised controlled trial of effect of raw and holder pasteurised human milk and of formula supplements on incidence of neonatal infection. Lancet. 1984;2(8412):1111-3. | Country
1644 | Narayanan, I.,Singh, S.,Mathur, R.,Jain, B. K. Ear infection and infant feeding practices. Indian J Pediatr. 1989;56(3):399-402. | Country
1645 | Narese, F.,Puccio, G.,Mazzucco, W.,Falzone, A.,Venturella, V.,Narese, D.,Capra, E. Earlier appearance of the ossification center of the femoral head in breast-fed versus formula-fed infants. Nutrition. 2011;27(11-12):1108-11. | Study design
1646 | Nascimento Souza, Maria Helena,Aparecida Barbosa Nogueira, Josiê Neiber,Domingues Sodré, Vitória Regina. MONITORING THE NUTRITIONAL AND HEALTH STATUS OF CHILDREN WHO ATTEND A COMMUNITY NURSERY. Journal of Nursing UFPE / Revista de Enfermagem UFPE. 2015;9(5):7862-7868 7p. | Study design, Independent variable
1647 | Nassar, M. F.,Younis, N. T.,El-Arab, S. E.,Fawzi, F. A. Neuro-developmental outcome and brain-derived neurotrophic factor level in relation to feeding practice in early infancy. Matern Child Nutr. 2011;7(2):188-97. | Study design
1648 | Nauta, A. Specific nutritional concepts & clinical evidence in the management of allergy. Asian Pacific Journal of Allergy and Immunology. 2012;30(4 SUPPL):S21-S24. | Study design
1649 | Navarro, J. I.,Sigulem, D. M.,Ferraro, A. A.,Polanco, J. J.,Barros, A. J. The double task of preventing malnutrition and overweight: a quasi-experimental community-based trial. BMC Public Health. 2013;13:212. | Independent variable
1650 | Nelson, C. M.,Innis, S. M. Plasma lipoprotein fatty acids are altered by the positional distribution of fatty acids in infant formula triacylglycerols and human milk. Am J Clin Nutr. 1999;70(1):62-9. | Group size
1651 | Nelson, C. M.,Innis, S. M.,Walsen, P.,Whitfield, M. Prospective measures of visual and cognitive development in term gestation breast-fed and formula-fed infants to 18 months of age. Pediatric research. 2002;2:315a. | Peer review
1652 | Nelson, E. A.,Yu, L. M.,Wong, D.,Wong, H. Y.,Yim, L. Rolling over in infants: age, ethnicity, and cultural differences. Dev Med Child Neurol. 2004;46(10):706-9. | Group size
1653 | Nelson, J. D. Prevention of gastrointestinal infections. Pediatr Infect Dis. 1985;4(4):431-4. | Study design, Independent variable
1654 | Nelson, M. C.,Gordon-Larsen, P.,Adair, L. S. Are adolescents who were breast-fed less likely to be overweight? Analyses of sibling pairs to reduce confounding. Epidemiology. 2005;16(2):247-53. | Included for systematic reviews not completed
1655 | Nelson, S. E.,Rogers, R. R.,Ziegler, E. E.,Fomon, S. J. Gain in weight and length during early infancy. Early Hum Dev. 1989;19(4):223-39. | Included for systematic reviews not completed
1656 | Nelson, S.,Albert, J. M.,Soderling, E.,Malik, A.,Curtan, S.,Geng, C.,Milgrom, P. Increased number of teeth predict acquisition of mutans streptococci in infants. Eur J Oral Sci. 2014;122(5):346-52. | Included for systematic reviews not completed
1657 | Nentwich, I.,Michkova, E.,Nevoral, J.,Urbanek, R.,Szepfalusi, Z. Cow’s milk-specific cellular and humoral immune responses and atopy skin symptoms in infants from atopic families fed a partially (pHF) or extensively (eHF) hydrolyzed infant formula. Allergy. 2001;56(12):1144-56. | Group size
1658 | Nery Cde, G.,Buranello, F. S.,Pereira, C.,Di Francesco, R. C. Otitis media with effusion and dental occlusion: is there any relationship?. Eur J Paediatr Dent. 2010;11(3):132-6. | Independent variable, Health status
1659 | Neutzling, M. B.,Hallal, P. R.,Araujo, C. L.,Horta, B. L.,Vieira Mde, F.,Menezes, A. M.,Victora, C. G. Infant feeding and obesity at 11 years: prospective birth cohort study. Int J Pediatr Obes. 2009;4(3):143-9. | Included for systematic reviews not completed
1660 | Neves, A. B.,Lobo, L. A.,Pinto, K. C.,Pires, E. S.,Requejo, M.,Maia, L. C.,Antonio, A. G. Comparison between Clinical Aspects and Salivary Microbial Profile of Children with and without Early Childhood Caries: A Preliminary Study. J Clin Pediatr Dent. 2015;39(3):209-14. | Study design
1661 | Newburg, D. S.,Ruiz-Palacios, G. M.,Altaye, M.,Chaturvedi, P.,Guerrero, M. L.,Meinzen-Derr, J. K.,Morrow, A. L. Human milk alphal,2-linked fucosylated oligosaccharides decrease risk of diarrhea due to stable toxin of E. coli in breastfed infants. Adv Exp Med Biol. 2004;554:457-61. | Independent variable
1662 | Newman, J. How breast milk protects newborns. Sci Am. 1995;273(6):76-9. | Study design
1663 | Ng, S. C.,Chong, Y. S.,Rauff, M.,Myo, Z. M.,Nurfarah, C.,Deurenberg, P. R. The influence of breast feeding compared to formula feeding on infant adiposity. Ann Acad Med Singapore. 2004;33(5 Suppl):S75. | Study design
1664 | Ng, S. C.,Tang, W.,Leong, R. W.,Chen, M.,Ko, Y.,Studd, C.,Niewiadomski, O.,Bell, S.,Kamm, M. A.,de Silva, H. J.,Kasturiratne, A.,Senanayake, Y. U.,Ooi, C. J.,Ling, K. L.,Ong, D.,Goh, K. L.,Hilmi, I.,Ouyang, Q.,Wang, Y. F.,Hu, P.,Zhu, Z.,Zeng, Z.,Wu, K.,Wang, X.,Xia, B.,Li, J.,Pisespongsa, P.,Manatsathit, S.,Aniwan, S.,Simadibrata, M.,Abdullah, M.,Tsang, S. W.,Wong, T. C.,Hui, A. J.,Chow, C. M.,Yu, H. H.,Li, M. F.,Ng, K. K.,Ching, J.,Wu, J. C.,Chan, F. K.,Sung, J. J. Environmental risk factors in inflammatory bowel disease: a population-based case-control study in Asia-Pacific. Gut. 2015;64(7):1063-71. | Independent variable
1665 | Ngale, K. M.,Santos, I. S.,Gonzalez-Chica, D. A.,de Barros, A. J.,Matijasevich, A. Bed-sharing and risk of hospitalisation due to pneumonia and diarrhoea in infancy: the 2004 Pelotas Birth Cohort. J Epidemiol Community Health. 2013;67(3):245-9. | Included for systematic reviews not completed
1666 | Ngamphaiboon, J. Food allergy and wheezing. Southeast Asian J Trop Med Public Health. 2014;45 Suppl 1:95-9. | Study design
1667 | Ngamphaiboon, J.,Tansupapol, C.,Chatchatee, P. The efficacy of partially hydrolyzed formulas for allergy prevention in children under five years. Asian Biomedicine. 2009;3(3):245-254. | Dependent variable
1668 | Nguyen, N. D.,Allen, J. R.,Peat, J. K.,Beal, P.,Webster, B. H.,Gaskin, K. J. Iron status of young Vietnamese children in Australia. J Paediatr Child Health. 2004;40(8):424-9. | Study design, Independent variable
1669 | Nguyen, N. D.,Allen, J. R.,Peat, J. K.,Schofield, W. N.,Nossar, V.,Eisenbruch, M.,Gaskin, K. J. Growth and feeding practices of Vietnamese infants in Australia. Eur J Clin Nutr. 2004;58(2):356-62. | Independent variable
1670 | Nicolai, A.,Nenna, R.,Stefanelli, P.,Carannante, A.,Schiavariello, C.,Pierangeli, A.,Scagnolari, C.,Moretti, C.,Papoff, P.,Bonci, E.,Ferrara, M.,Papasso, S.,Midulla, F. Bordetella pertussis in infants hospitalized for acute respiratory symptoms remains a concern. BMC Infect Dis. 2013;13:526. | Group size
1671 | Nicoll, A.,Williams, A. Breast feeding. Arch Dis Child. 2002;87(2):91-2. | Study design
1672 | Niegel, S.,Ystrom, E.,Hagtvet, K. A.,Vollrath, M. E. Difficult temperament, breastfeeding, and their mutual prospective effects: the Norwegian Mother and Child Cohort Study. J Dev Behav Pediatr. 2008;29(6):458-62. | Independent variable
1673 | Nielsen, G. A.,Thomsen, B. L.,Michaelsen, K. F. Influence of breastfeeding and complementary food on growth between 5 and 10 months. Acta Paediatr. 1998;87(9):911-7. | Included for systematic reviews not completed
1674 | Nielsen, S. B.,Reilly, J. J.,Fewtrell, M. S.,Eaton, S.,Grinham, J.,Wells, J. C. Adequacy of milk intake during exclusive breastfeeding: a longitudinal study. Pediatrics. 2011;128(4):e907-14. | Dependent variable
1675 | Niemela, A.,Jarvenpaa, A. L. Is breastfeeding beneficial and maternal smoking harmful to the cognitive development of children?. Acta Paediatr. 1996;85(10):1202-6. | Included for systematic reviews not completed
1676 | Niemela, M.,Uhari, M.,Mottonen, M. A pacifier increases the risk of recurrent acute otitis media in children in day care centers. Pediatrics. 1995;96(5 Pt 1):884-8. | Included for systematic reviews not completed
1677 | Nikpour, S.,Rahimian, Sh,Shokrabi, S.,Haghani, H. Related Factors of Acute Leukemia in Children and the Role of Breast Feeding. Iranian Journal of Endocrinology & Metabolism. 2012;14(1):63-97 35p. | Language
1678 | Nishimura, M.,Oda, T.,Kariya, N.,Matsumura, S.,Shimono, T. Using a caries activity test to predict caries risk in early childhood. J Am Dent Assoc. 2008;139(1):63-71. | Included for systematic reviews not completed
1679 | Nishimura, T.,Suzue, J.,Kaji, H. Breastfeeding reduces the severity of respiratory syncytial virus infection among young infants: a multi-center prospective study. Pediatr Int. 2009;51(6):812-6. | Included for systematic reviews not completed
1680 | Nnanyelugo, D. O. Nutritional practices and food intake measurements and their relationship to socio-economic grouping, location and their apparent nutritional adequacy in children. Appetite. 1982;3(3):229-41. | Country
1681 | Noda, M.,Sato, N.,Tanaka, T. Growth failure starts from early infancy in children with short stature at age 6. Clinical Pediatric Endocrinology. 2015;24(1):1-10. | Study design
1682 | Nolan, L.,Goel, V. Sociodemographic factors related to breastfeeding in Ontario: results from the Ontario Health Survey. Can J Public Health. 1995;86(5):309-12. | Study design
1683 | Nommsen-Rivers, L. A. Does breastfeeding protect against infant mortality in the United States?. J Hum Lact. 2004;20(3):357-8. | Study design
1684 | Nossar, V.,Hudson, D. Improving health outcomes for children by home visiting. Medicine Today. 2001;2(8):135-136. | Study design
1685 | Nott, S. Some faults on feeding. Midwife Health Visit Community Nurse. 1985;21(6):201-2. | Study design
1686 | Novotny, R.,Daida, Y. G.,Grove, J. S.,Acharya, S.,Vogt, T. M. Formula feeding in infancy is associated with adolescent body fat and earlier menarche. Cell Mol Biol (Noisy-le-grand). 2003;49(8):1289-93. | Study design
1687 | Novotny, R.,Mata, L. J. Breast milk consumption in rural Costa Rica. Arch Latinoam Nutr. 1983;33(2):377-86. | Group size
1688 | Nuesslein, T. G.,Beckers, D.,Rieger, C. H. Cotinine in meconium indicates risk for early respiratory tract infections. Hum Exp Toxicol. 1999;18(4):283-90. | Independent variable
1689 | Nunes, A. M.,Alves, C. M.,Borba de Araujo, F.,Ortiz, T. M.,Ribeiro, M. R.,Silva, A. A.,Ribeiro, C. C. Association between prolonged breast-feeding and early childhood caries: a hierarchical approach. Community Dent Oral Epidemiol. 2012;40(6):542-9. | Study design
1690 | Nutrition for mother and child. Nurs J India. 1990;81(6):181-8. | Study design
1691 | Nutritional adequacy of breast feeding. Nutr Rev. 1980;38:145-7. | Study design
1692 | Nwaru, B. I.,Erkkola, M.,Ahonen, S.,Kaila, M.,Haapala, A. M.,Kronberg-Kippila, C.,Salmelin, R.,Veijola, R.,Ilonen, J.,Simell, O.,Knip, M.,Virtanen, S. M.. Age at the introduction of solid foods during the first year and allergic sensitization at age 5 years. Pediatrics. 2010;125(1):50-9. | Dependent variable
1693 | Nwaru, B. I.,Takkinen, H. M.,Niemela, O.,Kaila, M.,Erkkola, M.,Ahonen, S.,Tuomi, H.,Haapala, A. M.,Kenward, M. G.,Pekkanen, J.,Lahesmaa, R.,Kere, J.,Simell, O.,Veijola, R.,Ilonen, J.,Hyoty, H.,Knip, M.,Virtanen, S. M.. Introduction of complementary foods in infancy and atopic sensitization at the age of 5 years: timing and food diversity in a Finnish birth cohort. Allergy. 2013;68(4):507-16. | Dependent variable
1694 | Nylander, G.,Lindemann, R.,Helsing, E.,Bendvold, E. Unsupplemented breastfeeding in the maternity ward. Positive long-term effects. Acta Obstet Gynecol Scand. 1991;70(3):205-9. | Study design, Independent variable
1695 | Obel, C.,Henriksen, T. B.,Hedegaard, M.,Secher, N. J.,Ostergaard, J. Smoking during pregnancy and babbling abilities of the 8-month-old infant. Paediatr Perinat Epidemiol. 1998;12(1):37-48. | Independent variable
1696 | Ochoa, M. C.,Moreno-Aliaga, M. J.,Martinez-Gonzalez, M. A.,Martinez, J. A.,Marti, A. Predictor factors for childhood obesity in a Spanish case-control study. Nutrition. 2007;23(5):379-84. | Included for systematic reviews not completed
1697 | O’Connell, J. M.,Dibley, M. J.,Sierra, J.,Wallace, B.,Marks, J. S.,Yip, R. Growth of vegetarian children: The Farm Study. Pediatrics. 1989;84(3):475-81. | Independent variable
1698 | O’Connor, P. A. Clouds, skin color, and rickets. Pediatrics. 1980;66(2):332. | Study design
1699 | Oddy, W. H. Breastfeeding and asthma in children. A prospective cohort study. Adv Exp Med Biol. 2000;478:393-4. | Study design
1700 | Oddy, W. H. Breastfeeding and asthma in children: findings from a West Australian study. Breastfeed Rev. 2000;8(1):5-11. | Redundant data
1701 | Oddy, W. H.,de Klerk, N. H.,Sly, P. D.,Holt, P. G.. The effects of respiratory infections, atopy, and breastfeeding on childhood asthma. Eur Respir J. 2002;19(5):899-905. | Included for systematic reviews not completed
1702 | Oddy, W. H.,Halonen, M.,Martinez, F. D.,Lohman, I. C.,Stern, D. A.,Kurzius-Spencer, M.,Guerra, S.,Wright, A. L. TGF-beta in human milk is associated with wheeze in infancy. J Allergy Clin Immunol. 2003;112(4):723-8. | Dependent variable
1703 | Oddy, W. H.,Kendall, G. E.,Blair, E.,de Klerk, N. H.,Silburn, S.,Zubrick, S. Breastfeeding and cognitive development in children. Adv Exp Med Biol. 2004;554:365-9. | Included for systematic reviews not completed
1704 | Oddy, W. H.,Kendall, G. E.,Blair, E.,De Klerk, N. H.,Stanley, F. J.,Landau, L. I.,Silburn, S.,Zubrick, S. Breast feeding and cognitive development in childhood: a prospective birth cohort study. Paediatr Perinat Epidemiol. 2003;17(1):81-90. | Included for systematic reviews not completed
1705 | Oddy, W. H.,Kendall, G. E.,Li, J.,Jacoby, P.,Robinson, M.,de Klerk, N. H.,Silburn, S. R.,Zubrick, S. R.,Landau, L. I.,Stanley, F. J. The long-term effects of breastfeeding on child and adolescent mental health: a pregnancy cohort study followed for 14 years. J Pediatr. 2010;156(4):568-74. | Included for systematic reviews not completed
1706 | Oddy, W. H.,Kickett-Tucker, C.,De Maio, J.,Lawrence, D.,Cox, A.,Silburn, S. R.,Stanley, F. J.,Zubrick, S. R. The association of infant feeding with parent-reported infections and hospitalisations in the West Australian Aboriginal Child Health Survey. Aust N Z J Public Health. 2008;32(3):207-15. | Included for systematic reviews not completed
1707 | Oddy, W. H.,Li, J.,Whitehouse, A. J. O.,Zubrick, S. R.,Malacova, E. Breastfeeding duration and academic achievement at 10 years. Pediatrics. 2011;127(1):e137-e145. | Included for systematic reviews not completed
1708 | Oddy, W. H.,Mori, T. A.,Huang, R. C.,Marsh, J. A.,Pennell, C. E.,Chivers, P. T.,Hands, B. P.,Jacoby, P.,Rzehak, P.,Koletzko, B. V.,Beilin, L. J. Early infant feeding and adiposity risk: From infancy to adulthood. Annals of Nutrition and Metabolism. 2014;64(3-4):262-270. | Included for systematic reviews not completed
1709 | Oddy, W. H.,Peat, J. K.,de Klerk, N. H. Maternal asthma, infant feeding, and the risk of asthma in childhood. J Allergy Clin Immunol. 2002;110(1):65-7. | Independent variable
1710 | Oddy, W. H.,Robinson, M.,Kendall, G. E.,Li, J.,Zubrick, S. R.,Stanley, F. J. Breastfeeding and early child development: a prospective cohort study. Acta Paediatr. 2011;100(7):992-9. | Included for systematic reviews not completed
1711 | Oddy, W. H.,Scott, J. A.,Graham, K. I.,Binns, C. W. Breastfeeding influences on growth and health at one year of age. Breastfeed Rev. 2006;14(1):15-23. | Included for systematic reviews not completed
1712 | Oddy, W. H.,Sherriff, J. L.,de Klerk, N. H.,Kendall, G. E.,Sly, P. D.,Beilin, L. J.,Blake, K. B.,Landau, L. I.,Stanley, F. J.. The relation of breastfeeding and body mass index to asthma and atopy in children: a prospective cohort study to age 6 years. Am J Public Health. 2004;94(9):1531-7. | Included for systematic reviews not completed
1713 | Oddy, W. H.,Sly, P. D.,de Klerk, N. H.,Landau, L. I.,Kendall, G. E.,Holt, P. G.,Stanley, F. J. Breast feeding and respiratory morbidity in infancy: a birth cohort study. Arch Dis Child. 2003;88(3):224-8. | Included for systematic reviews not completed
1714 | Oddy, W. H.,Smith, G. J.,Jacoby, P. A possible strategy for developing a model to account for attrition bias in a longitudinal cohort to investigate associations between exclusive breastfeeding and overweight and obesity at 20 years. Ann Nutr Metab. 2014;65(2-3):234-5. | Study design, Independent variable
1715 | Odelram, H.,Vanto, T.,Jacobsen, L.,Kjellman, N. I. Whey hydrolysate compared with cow’s milk-based formula for weaning at about 6 months of age in high allergy-risk infants: effects on atopic disease and sensitization. Allergy. 1996;51(3):192-5. | Independent variable
1716 | O’Donovan, S. M.,O’B Hourihane J,Murray, D. M.,Kenny, L. C.,Khashan, A. S.,Chaoimh, C. N.,Irvine, A. D.,Kiely, M. Neonatal adiposity increases the risk of atopic dermatitis during the first year of life. J Allergy Clin Immunol. 2015. | Independent variable
1717 | Ogston, S. A.,Florey, C. D.,Walker, C. H. Association of infant alimentary and respiratory illness with parental smoking and other environmental factors. J Epidemiol Community Health. 1987;41(1):21-5. | Included for systematic reviews not completed
1718 | Ohlund, I.,Hornell, A.,Lind, T.,Hernell, O.. Dietary fat in infancy should be more focused on quality than on quantity. Eur J Clin Nutr. 2008;62(9):1058-64. | Dependent variable
1719 | Oken, E.,Osterdal, M. L.,Gillman, M. W.,Knudsen, V. K.,Halldorsson, T. I.,Strom, M.,Bellinger, D. C.,Hadders-Algra, M.,Michaelsen, K. F.,Olsen, S. F. Associations of maternal fish intake during pregnancy and breastfeeding duration with attainment of developmental milestones in early childhood: a study from the Danish National Birth Cohort. Am J Clin Nutr. 2008;88(3):789-96. | Included for systematic reviews not completed
1720 | Olaya, G. A.,Lawson, M.,Fewtrell, M. S. Efficacy and safety of new complementary feeding guidelines with an emphasis on red meat consumption: a randomized trial in Bogota, Colombia. Am J Clin Nutr. 2013;98(4):983-93. | Independent variable
1721 | Oliveira, A. F.,Chaves, A. M.,Rosenblatt, A. The influence of enamel defects on the development of early childhood caries in a population with low socioeconomic status: a longitudinal study. Caries Res. 2006;40(4):296-302. | Independent variable
1722 | Oliveira, E. A.,Bertoldi, A. D.,Domingues, M. R.,Santos, I. S.,Barros, A. J. Factors associated to medicine use among children from the 2004 Pelotas Birth Cohort (Brazil). Rev Saude Publica. 2012;46(3):487-96. | Dependent variable
1723 | Ollila, P.,Larmas, M. A seven-year survival analysis of caries onset in primary second molars and permanent first molars in different caries risk groups determined at age two years. Acta Odontol Scand. 2007;65(1):29-35. | Included for systematic reviews not completed
1724 | Ölmez, S.,Uzamiş, M. Risk factors of early childhood caries in Turkish children. Turkish Journal of Pediatrics. 2002;44(3):230-236. | Study design
1725 | Olmez, S.,Uzamis, M.,Erdem, G. Association between early childhood caries and clinical, microbiological, oral hygiene and dietary variables in rural Turkish children. Turk J Pediatr. 2003;45(3):231-6. | Study design
1726 | Olson, C. M.,Baker, I. R.,Demment, M. M.,Graham, M. L.,May, J. J.,Strawderman, M. S.,Wells, N. M. The healthy start partnership: an approach to obesity prevention in young families. Fam Community Health. 2014;37(1):74-85. | Independent variable
1727 | Ong, K. K.,Ahmed, M. L.,Sherriff, A.,Woods, K. A.,Watts, A.,Golding, J.,Dunger, D. B. Cord blood leptin is associated with size at birth and predicts infancy weight gain in humans. ALSPAC Study Team. Avon Longitudinal Study of Pregnancy and Childhood. J Clin Endocrinol Metab. 1999;84(3):1145-8. | Independent variable
1728 | Ong, K. K.,Emmett, P. M.,Noble, S.,Ness, A.,Dunger, D. B. Dietary energy intake at the age of 4 months predicts postnatal weight gain and childhood body mass index. Pediatrics. 2006;117(3):e503-8. | Independent variable
1729 | Ong, K. K.,Preece, M. A.,Emmett, P. M.,Ahmed, M. L.,Dunger, D. B. Size at birth and early childhood growth in relation to maternal smoking, parity and infant breast-feeding: longitudinal birth cohort study and analysis. Pediatr Res. 2002;52(6):863-7. | Included for systematic reviews not completed
1730 | Oppitz, I. N.,Cesar, J. A.,Neumann, N. A. Overweight among children under five years of age in municipalities of the semiarid region. Rev Bras Epidemiol. 2014;17(4):860-72. | Study design
1731 | Orakzai, S. A.,Siddiqui, K. A.,Ayub, M.,Saeed, A. K. Serum proteins in infants. J Pak Med Assoc. 1987;37(10):251-5. | Study design
1732 | Orozco, A. C.,Munoz, A. M.,Velasquez, C. M.,Uscategui, R. M.,Parra, M. V.,Patino, F. A.,Manjarres, L. M.,Parra, B. E.,Estrada, A.,Agudelo, G. M. Variant in CAPN10 gene and environmental factors show evidence of association with excess weight among young people in a Colombian population. Biomedica. 2014;34(4):546-55. | Study design
1733 | Orr P,McDonald S,Milley D,Brown R. Bronchiolitis in Inuit children from a Canadian central arctic community, 1995-1996. Int J Circumpolar Health. 2001;60:649-58. | Included for systematic reviews not completed
1734 | Ortega-Garcia, J. A.,Ferris-Tortajada, J.,Torres-Cantero, A. M.,Soldin, O. P.,Torres, E. P.,Fuster-Soler, J. L.,Lopez-Ibor, B.,Madero-Lopez, L. Full breastfeeding and paediatric cancer. J Paediatr Child Health. 2008;44(1-2):10-3. | Dependent variable
1735 | O’Ryan, M. L.,Lucero, Y.,Rabello, M.,Mamani, N.,Salinas, A. M.,Pena, A.,Torres-Torreti, J. P.,Mejias, A.,Ramilo, O.,Suarez, N.,Reynolds, H. E.,Orellana, A.,Lagomarcino, A. J. Persistent and transient Helicobacter pylori infections in early childhood. Clin Infect Dis. 2015;61(2):211-8. | Dependent variable
1736 | Ostrom, K. M.,Cordle, C. T.,Schaller, J. P.,Winship, T. R.,Thomas, D. J.,Jacobs, J. R.,Blatter, M. M.,Cho, S.,Gooch, W. M., 3rd,Granoff, D. M.,Faden, H.,Pickering, L. K. Immune status of infants fed soy-based formulas with or without added nucleotides for 1 year: part 1: vaccine responses, and morbidity. J Pediatr Gastroenterol Nutr. 2002;34(2):137-44. | Included for systematic reviews not completed
1737 | O’Sullivan, D. M.,Tinanoff, N. Social and biological factors contributing to caries of the maxillary anterior teeth. Pediatr Dent. 1993;15(1):41-4. | Study design
1738 | Oti-Boateng, P.,Seshadri, R.,Petrick, S.,Gibson, R. A.,Simmer, K. Iron status and dietary iron intake of 6-24-month-old children in Adelaide. J Paediatr Child Health. 1998;34(3):250-3. | Study design
1739 | O’Tierney, P. F.,Barker, D. J.,Osmond, C.,Kajantie, E.,Eriksson, J. G. Duration of breast-feeding and adiposity in adult life. J Nutr. 2009;139(2):422S-5S. | Included for systematic reviews not completed
1740 | Ou, X.,Andres, A.,Cleves, M. A.,Pivik, R. T.,Snow, J. H.,Ding, Z.,Badger, T. M. Sex-specific association between infant diet and white matter integrity in 8-y-old children. Pediatr Res. 2014;76(6):535-43. | Dependent variable
1741 | Oulis, C. J.,Berdouses, E. D.,Vadiakas, G.,Lygidakis, N. A. Feeding practices of Greek children with and without nursing caries. Pediatr Dent. 1999;21(7):409-16. | Study design
1742 | Ounsted, M. K.,Moar, V. A.,Scott, A. Small-for-dates babies at the age of four years: health, handicap and developmental status. Early Hum Dev. 1983;8(3-4):243-58. | Independent variable
1743 | Ounsted, M.,Moar, V. A.,Cockburn, J.,Redman, C. W. Factors associated with the intellectual ability of children born to women with high risk pregnancies. Br Med J (Clin Res Ed). 1984;288(6423):1038-41. | Group size
1744 | Ovsenik, M. Incorrect orofacial functions until 5 years of age and their association with posterior crossbite. Am J Orthod Dentofacial Orthop. 2009;136(3):375-81. | Study design, Independent variable
1745 | Owen, G. M.,Garry, P. J.,Hooper, E. M.,Gilbert, B. A.,Pathak, D. Iron nutriture of infants exclusively breast-fed the first five months. J Pediatr. 1981;99(2):237-40. | Independent variable
1746 | Owen, M. J.,Baldwin, C. D.,Swank, P. R.,Pannu, A. K.,Johnson, D. L.,Howie, V. M. Relation of infant feeding practices, cigarette smoke exposure, and group child care to the onset and duration of otitis media with effusion in the first two years of life. J Pediatr. 1993;123(5):702-11. | Included for systematic reviews not completed
1747 | Ozden, T. A.,Gokcay, G.,Cantez, M. S.,Durmaz, O.,Issever, H.,Omer, B.,Saner, G. Copper, zinc and iron levels in infants and their mothers during the first year of life: a prospective study. BMC Pediatr. 2015;15(1):157. | Study design, Independent variable
1748 | Ozmert, E. N.,Kale-Cekinmez, E.,Yurdakok, K.,Sekerel, B. E. Determinants of allergic signs and symptoms in 24- 48-month-old Turkish children. Turk J Pediatr. 2009;51(2):103-9. | Study design
1749 | Ozmert, E. N.,Yurdakok, K.,Soysal, S.,Kulak-Kayikci, M. E.,Belgin, E.,Ozmert, E.,Laleli, Y.,Saracbasi, O. Relationship between physical, environmental and sociodemographic factors and school performance in primary schoolchildren. J Trop Pediatr. 2005;51(1):25-32. | Study design
1750 | Pacheco, G.,Hedges, M.,Schilling, C.,Morton, S. Pre- and postnatal drivers of childhood intelligence: evidence from Singapore. J Biosoc Sci. 2013;45(1):41-56. | Study design
1751 | Paine, B. J.,Makrides, M.,Gibson, R. A. Duration of breast-feeding and Bayley’s Mental Developmental Index at 1 year of age. J Paediatr Child Health. 1999;35(1):82-5. | Study design
1752 | Paine, R.,Coble, R. J. Breast-feeding and infant health in a rural US community. Am J Dis Child. 1982;136(1):36-8. | Independent variable
1753 | Palloni, A.,Aguirre, G. P.,Lastiri, S. The effects of breast-feeding and the pace of childbearing on early childhood mortality in Mexico. Bull Pan Am Health Organ. 1994;28(2):93-111. | Study design, Independent variable
1754 | Palloni, A.,Tienda, M. The effects of breastfeeding and pace of childbearing on mortality at early ages. Demography. 1986;23(1):31-52. | Study design
1755 | Palma, G. D.,Capilla, A.,Nova, E.,Castillejo, G.,Varea, V.,Pozo, T.,Garrote, J. A.,Polanco, I.,Lopez, A.,Ribes-Koninckx, C.,Marcos, A.,Garcia-Novo, M. D.,Calvo, C.,Ortigosa, L.,Pena-Quintana, L.,Palau, F.,Sanz, Y. Influence of milk-feeding type and genetic risk of developing coeliac disease on intestinal microbiota of infants: the PROFICEL study. PLoS One. 2012;7(2):e30791. | Dependent variable
1756 | Palmer, M. M.,VandenBerg, K. A. A closer look at neonatal sucking. Neonatal Netw. 1998;17(2):77-9. | Study design
1757 | Palti, H.,Mansbach, I.,Pridan, H.,Adler, B.,Palti, Z. Episodes of illness in breast-fed and bottle-fed infants in Jerusalem. Isr J Med Sci. 1984;20(5):395-9. | Independent variable
1758 | Palvo, F.,Toledo, E. C.,Menin, A. M.,Jorge, P. P.,Godoy, M. F.,Sole, D. Risk factors of childhood asthma in Sao Jose do Rio Preto, Sao Paulo, Brazil. J Trop Pediatr. 2008;54(4):253-7. | Study design
1759 | Panagiotakos, D. B.,Papadimitriou, A.,Anthracopoulos, M. B.,Konstantinidou, M.,Antonogeorgos, G.,Fretzayas, A.,Priftis, K. N. Birthweight, breast-feeding, parental weight and prevalence of obesity in schoolchildren aged 10-12 years, in Greece; the Physical Activity, Nutrition and Allergies in Children Examined in Athens (PANACEA) study. Pediatr Int. 2008;50(4):563-8. | Study design
1760 | Panico, L.,Stuart, B.,Bartley, M.,Kelly, Y. Asthma trajectories in early childhood: identifying modifiable factors. PLoS One. 2014;9(11):e111922. | Dependent variable
1761 | Papandreou, D.,Malindretos, P.,Rousso, I. Risk factors for childhood obesity in a Greek paediatric population. Public Health Nutr. 2010;13(10):1535-9. | Study design
1762 | Papenburg, J.,Hamelin, M. E.,Ouhoummane, N.,Carbonneau, J.,Ouakki, M.,Raymond, F.,Robitaille, L.,Corbeil, J.,Caouette, G.,Frenette, L.,De Serres, G.,Boivin, G. Comparison of risk factors for human metapneumovirus and respiratory syncytial virus disease severity in young children. J Infect Dis. 2012;206(2):178-89. | Health status
1763 | Papp, L. M. Longitudinal associations between breastfeeding and observed mother-child interaction qualities in early childhood. Child Care Health Dev. 2014;40(5):740-6. | Included for systematic reviews not completed
1764 | Paradise, J. L.,Rockette, H. E.,Colborn, D. K.,Bernard, B. S.,Smith, C. G.,Kurs-Lasky, M.,Janosky, J. E. Otitis media in 2253 Pittsburgh-area infants: prevalence and risk factors during the first two years of life. Pediatrics. 1997;99(3):318-33. | Included for systematic reviews not completed
1765 | Paricio Talayero JM,Lizan-Garcia M,Otero Puime A,Benlloch Muncharaz MJ,Beseler Soto B,Sanchez-Palomares M,Santos Serrano L,Rivera LL. Full breastfeeding and hospitalization as a result of infections in the first year of life. Pediatrics. 2006;118:e92-9. | Independent variable
1766 | Park, J.,Kim, H. S.,Chu, S. H.,Jekal, Y. S.,Lee, J. Y. The effect of predominant breast-feeding on the risk of obesity in Korean preschool children. Nurs Health Sci. 2015. | Study design
1767 | Park, M. J.,Namgung, R.,Kim, D. H.,Tsang, R. C. Bone mineral content is not reduced despite low vitamin D status in breast milk-fed infants versus cow’s milk based formula-fed infants. J Pediatr. 1998;132(4):641-5. | Group size
1768 | Park, S.,Kim, B. N.,Kim, J. W.,Shin, M. S.,Yoo, H. J.,Cho, S. C. Protective effect of breastfeeding with regard to children’s behavioral and cognitive problems. Nutr J. 2014;13(1):111. | Study design
1769 | Parsons, T. J.,Power, C.,Manor, O. Infant feeding and obesity through the lifecourse. Arch Dis Child. 2003;88(9):793-4. | Included for systematic reviews not completed
1770 | Paszkowski, J.,Lopatynski, J. Allergy to house dust mites in primary health care subjects with chronic or recurrent inflammatory states of respiratory system. Ann Univ Mariae Curie Sklodowska Med. 2002;57(1):522-30. | Health status
1771 | Patel, J. A.,Alvarez-Fernandez, P.,Jennings, K.,Loeffelholz, M.,McCormick, D.,Chonmaitree, T. Factors Affecting Staphylococcus aureus Colonization of the Nasopharynx in the First 6 Months of Life. Pediatr Infect Dis J. 2015;34(8):826-30. | Dependent variable
1772 | Patel, J. A.,Nair, S.,Revai, K.,Grady, J.,Saeed, K.,Matalon, R.,Block, S.,Chonmaitree, T. Association of proinflammatory cytokine gene polymorphisms with susceptibility to otitis media. Pediatrics. 2006;118(6):2273-9. | Study design, Dependent variable
1773 | Paterson, J. E.,Gao, W.,Sundborn, G.,Cartwright, S. Maternal self-report of oral health in six-year-old Pacific children from South Auckland, New Zealand. Community Dent Oral Epidemiol. 2011;39(1):19-28. | Included for systematic reviews not completed
1774 | Paterson, J.,Iusitini, L.,Gao, W. Child developmental assessment at two-years of age: data from the Pacific Islands Families Study. Pac Health Dialog. 2011;17(2):51-63. | Included for systematic reviews not completed
1775 | Patra, S.,Singh, V.,Kumar, P.,Chandra, J.,Dutta, A.,Tripathi, M. Demographic and clinical profile of children under two years of age with recurrent wheezing. J Coll Physicians Surg Pak. 2011;21(11):715-7. | Country
1776 | Patsourou, A.,Konstantinides, T.,Mantadakis, E.,Tsalkidis, A.,Zarras, C.,Balaska, A.,Simopoulos, K.,Chatzimichael, A. Growth of exclusively breastfed and self-weaned children of Greece aged 0-36 months. Breastfeed Med. 2012;7(6):521-5. | Study design
1777 | Patterson, C. C.,Carson, D. J.,Hadden, D. R.,Waugh, N. R.,Cole, S. K. A case-control investigation of perinatal risk factors for childhood IDDM in Northern Ireland and Scotland. Diabetes Care. 1994;17(5):376-81. | Independent variable
1778 | Patwari, A. K. Breastfeeding and atopy. Indian Pediatr. 1996;33(3):265-6. | Study design, Country
1779 | Paul A,Whitehead R. Infant feeding: the weighting game. Community Outlook. 1986:11-7. | Study design
1780 | Paul, K.,Dittrichova, J.,Papousek, H. Infant feeding behavior: development in patterns and motivation. Dev Psychobiol. 1996;29(7):563-76. | Group size
1781 | Pavic, I.,Jurkovic, M.,Pastar, Z. Risk factors for acute respiratory tract infections in children. Coll Antropol. 2012;36(2):539-42. | Study design
1782 | Pearce, M. S.,Birrell, F. N.,Francis, R. M.,Rawlings, D. J.,Tuck, S. P.,Parker, L. Lifecourse study of bone health at age 49-51 years: the Newcastle thousand families cohort study. J Epidemiol Community Health. 2005;59(6):475-80. | Independent variable
1783 | Pearson, Catherine. Study Finds Breastfeeding May Lower Alzheimer’s Risk. Inside Childbirth Education. 2013:9-9 1p. | Study design
1784 | Peat, J. K. Can asthma be prevented? Evidence from epidemiological studies of children in Australia and New Zealand in the last decade. Clin Exp Allergy. 1998;28(3):261-5. | Study design
1785 | Peat, J. K.,Allen, J.,Oddy, W.,Webb, K. Breastfeeding and asthma: appraising the controversy. Pediatr Pulmonol. 2003;35(5):331-4. | Study design
1786 | Pedersen, C. B.,Zachau-Christiansen, B. Otitis media in Greenland children: acute, chronic and secretory otitis media in three- to eight-year-olds. J Otolaryngol. 1986;15(6):332-5. | Study design
1787 | Pei, Z.,Heinrich, J.,Fuertes, E.,Flexeder, C.,Hoffmann, B.,Lehmann, I.,Schaaf, B.,von Berg, A.,Koletzko, S. Cesarean delivery and risk of childhood obesity. J Pediatr. 2014;164(5):1068-1073 e2. | Included for systematic reviews not completed
1788 | Pelayo, L.,Nunez, F. A.,Rojas, L.,Wilke, H.,Furuseth Hansen, E.,Mulder, B.,Gjerde, B.,Robertson, L. Molecular and epidemiological investigations of cryptosporidiosis in Cuban children. Ann Trop Med Parasitol. 2008;102(8):659-69. | Health status
1789 | Peltzer, K.,Mongkolchati, A.,Satchaiyan, G.,Rajchagool, S.,Pimpak, T. Sociobehavioral factors associated with caries increment: a longitudinal study from 24 to 36 months old children in Thailand. Int J Environ Res Public Health. 2014;11(10):10838-50. | Included for systematic reviews not completed
1790 | Penders, J.,Gerhold, K.,Stobberingh, E. E.,Thijs, C.,Zimmermann, K.,Lau, S.,Hamelmann, E. Establishment of the intestinal microbiota and its role for atopic dermatitis in early childhood. J Allergy Clin Immunol. 2013;132(3):601-607 e8. | Independent variable, Dependent variable
1791 | Peneau, S.,Hercberg, S.,Rolland-Cachera, M. F. Breastfeeding, early nutrition, and adult body fat. J Pediatr. 2014;164(6):1363-8. | Group size
1792 | Penn, A. H.,Carver, L. J.,Herbert, C. A.,Lai, T. S.,McIntire, M. J.,Howard, J. T.,Taylor, S. F.,Schmid-Schonbein, G. W.,Dobkins, K. R. Breast Milk Protects Against Gastrointestinal Symptoms in Infants at High Risk for Autism During Early Development. J Pediatr Gastroenterol Nutr. 2016;62(2):317-27. | Dependent variable
1793 | Penwell, A. Breastfeeding and newborn survival. Midwifery Today Int Midwife. 2012(101):51-3. | Study design
1794 | Perera, B. J. Preventive strategies for acute respiratory infections in children. Ceylon Med J. 2010;55(4):103-5. | Study design
1795 | Perera, B. J.,Ganesan, S.,Jayarasa, J.,Ranaweera, S. The impact of breastfeeding practices on respiratory and diarrhoeal disease in infancy: a study from Sri Lanka. J Trop Pediatr. 1999;45(2):115-8. | Study design, Dependent variable
1796 | Peres, K. G.,Cascaes, A. M.,Peres, M. A.,Demarco, F. F.,Santos, I. S.,Matijasevich, A.,Barros, A. J. Exclusive Breastfeeding and Risk of Dental Malocclusion. Pediatrics. 2015;136(1):e60-7. | Included for systematic reviews not completed
1797 | Peroni, D. G.,Piacentini, G. L.,Alfonsi, L.,Zerman, L.,Di Blasi, P.,Visona, G.,Nottegar, F.,Boner, A. L. Rhinitis in pre-school children: prevalence, association with allergic diseases and risk factors. Clin Exp Allergy. 2003;33(10):1349-54. | Study design
1798 | Persico, M.,Podoshin, L.,Fradis, M.,Golan, D.,Wellisch, G. Recurrent middle-ear infections in infants: the protective role of maternal breast feeding. Ear Nose Throat J. 1983;62(6):297-304. | Dependent variable, Health status
1799 | Persson, L. A. Infant feeding and growth--a longitudinal study in three Swedish communities. Ann Hum Biol. 1985;12(1):41-52. | Included for systematic reviews not completed
1800 | Persson, L. A.,Lundstrom, M.,Lonnerdal, B.,Hernell, O. Are weaning foods causing impaired iron and zinc status in 1-year-old Swedish infants? A cohort study. Acta Paediatr. 1998;87(6):618-22. | Independent variable
1801 | Pesonen, M.,Kallio, M. J.,Ranki, A.,Siimes, M. A. Prolonged exclusive breastfeeding is associated with increased atopic dermatitis: a prospective follow-up study of unselected healthy newborns from birth to age 20 years. Clin Exp Allergy. 2006;36(8):1011-8. | Independent variable
1802 | Peters, D. C.,Worthington-Roberts, B. Infant feeding practices of middle-class breastfeeding and formula-feeding mothers. Birth. 1982;9(2):91-5. | Dependent variable
1803 | Peters, K. E.,Huang, J.,Vaughn, M. G.,Witko, C. Does breastfeeding contribute to the racial gap in reading and math test scores?. Ann Epidemiol. 2013;23(10):646-51. | Included for systematic reviews not completed
1804 | Peters, T. J.,Golding, J. The epidemiology of childhood eczema: II. Statistical analyses to identify independent early predictors. Paediatr Perinat Epidemiol. 1987;1(1):80-94. | Independent variable
1805 | Petherick, A. Development: Mother’s milk: A rich opportunity. Nature. 2010;468(7327):S5-7. | Study design
1806 | Petti, S.,Cairella, G.,Tarsitani, G. Rampant early childhood dental decay: an example from Italy. J Public Health Dent. 2000;60(3):159-66. | Study design
1807 | Pettitt, D. J.,Forman, M. R.,Hanson, R. L.,Knowler, W. C.,Bennett, P. H.. Breastfeeding and incidence of non-insulin-dependent diabetes mellitus in Pima Indians. Lancet. 1997;350(9072):166-8. | Independent variable
1808 | Pettitt, D. J.,Knowler, W. C. Long-term effects of the intrauterine environment, birth weight, and breast-feeding in Pima Indians. Diabetes Care. 1998;21 Suppl 2:B138-41. | Study design, Independent variable
1809 | Peyre, H.,Bernard, J. Y.,Forhan, A.,Charles, M. A.,De Agostini, M.,Heude, B.,Ramus, F.,Charles, M. A.,De Agostini, M.,Forhan, A.,Heude, B.,Ducimetière, P.,Kaminski, M.,Saurel-Cubizolles, M. J.,Dargent, P.,Fritel, X.,Larroque, B.,Lelong, N.,Marchand, L.,Nabet, C.,Annesi-Maesano, I.,Slama, R.,Goua, V.,Magnin, G.,Hankard, R.,Thiebaugeorges, O.,Schweitzer, M.,Foliguet, B.,Job-Spira, N. Predicting changes in language skills between 2 and 3 years in the EDEN mother-child cohort. PeerJ. 2014;2014(1). | Included for systematic reviews not completed
1810 | Pfluger, M.,Winkler, C.,Hummel, S.,Ziegler, A. G. Early infant diet in children at high risk for type 1 diabetes. Horm Metab Res. 2010;42(2):143-8. | Independent variable
1811 | Picciano, M. F.,Deering, R. H. The influence of feeding regimens on iron status during infancy. Am J Clin Nutr. 1980;33(4):746-53. | Independent variable
1812 | Picone, T. A.,Benson, J. D.,Moro, G.,Minoli, I.,Fulconis, F.,Rassin, D. K.,Raiha, N. C. Growth, serum biochemistries, and amino acids of term infants fed formulas with amino acid and protein concentrations similar to human milk. J Pediatr Gastroenterol Nutr. 1989;9(3):351-60. | Independent variable, Dependent variable
1813 | Piemontese, P.,Gianni, M. L.,Braegger, C. P.,Chirico, G.,Gruber, C.,Riedler, J.,Arslanoglu, S.,van Stuijvenberg, M.,Boehm, G.,Jelinek, J.,Roggero, P. Tolerance and safety evaluation in a large cohort of healthy infants fed an innovative prebiotic formula: a randomized controlled trial. PLoS One. 2011;6(11):e28010. | Included for systematic reviews not completed
1814 | Pinho, A. P.,Aerts, D.,Nunes, M. L. Risk factors for sudden infant death syndrome in a developing country. Rev Saude Publica. 2008;42(3):396-401. | Independent variable
1815 | Pinzon-Rondon, A. M.,Aguilera-Otalvaro, P.,Zarate-Ardila, C.,Hoyos-Martinez, A. Acute respiratory infection in children from developing nations: a multi-level study. Paediatr Int Child Health. 2015:2046905515y0000000021. | Study design
1816 | Pires, S. C.,Giugliani, E. R.,Caramez da Silva, F. Influence of the duration of breastfeeding on quality of muscle function during mastication in preschoolers: a cohort study. BMC Public Health. 2012;12(1):934. | Included for systematic reviews not completed
1817 | Pirila, S.,Saarinen-Pihkala, U. M.,Viljakainen, H.,Turanlahti, M.,Kajosaari, M.,Makitie, O.,Taskinen, M. Breastfeeding and determinants of adult body composition: a prospective study from birth to young adulthood. Horm Res Paediatr. 2012;77(5):281-90. | Included for systematic reviews not completed
1818 | Pirila, S.,Taskinen, M.,Viljakainen, H.,Kajosaari, M.,Turanlahti, M.,Saarinen-Pihkala, U. M.,Makitie, O. Infant milk feeding influences adult bone health: a prospective study from birth to 32 years. PLoS One. 2011;6(4):e19068. | Included for systematic reviews not completed
1819 | Pisacane, A.,De Vizia, B.,Valiante, A.,Vaccaro, F.,Russo, M.,Grillo, G.,Giustardi, A. Iron status in breast-fed infants. J Pediatr. 1995;127(3):429-31. | Group size
1820 | Pisacane, A.,Graziano, L.,Zona, G.,Granata, G.,Dolezalova, H.,Cafiero, M.,Coppola, A.,Scarpellino, B.,Ummarino, M.,Mazzarella, G. Breast feeding and acute lower respiratory infection. Acta Paediatr. 1994;83(7):714-8. | Study design, Health status
1821 | Pivik, R. T.,Andres, A.,Badger, T. M. Diet and gender influences on processing and discrimination of speech sounds in 3- and 6-month-old infants: a developmental ERP study. Dev Sci. 2011;14(4):700-12. | Included for systematic reviews not completed
1822 | Pivik, R. T.,Andres, A.,Badger, T. M. Effects of diet on early stage cortical perception and discrimination of syllables differing in voice-onset time: a longitudinal ERP study in 3 and 6 month old infants. Brain Lang. 2012;120(1):27-41. | Included for systematic reviews not completed
1823 | Pivik, R. T.,Andres, A.,Tennal, K. B.,Gu, Y.,Armbya, N.,Cleves, M. A.,Badger, T. M. Infant diet, gender and the normative development of vagal tone and heart period during the first two years of life. Int J Psychophysiol. 2013;90(3):311-20. | Dependent variable
1824 | Pivik, R. T.,Andres, A.,Tennal, K. B.,Gu, Y.,Cleves, M. A.,Badger, T. M. Infant diet, gender and the development of vagal tone stability during the first two years of life. Int J Psychophysiol. 2015;96(2):104-14. | Dependent variable
1825 | Pivik, R. T.,Dykman, R. A.,Jing, H.,Gilchrist, J. M.,Badger, T. M. Early infant diet and the omega 3 fatty acid DHA: effects on resting cardiovascular activity and behavioral development during the first half-year of life. Dev Neuropsychol. 2009;34(2):139-58. | Group size
1826 | Pivik, R. T.,Dykman, R. A.,Jing, H.,Gilchrist, J. M.,Badger, T. M. The influence of infant diet on early developmental changes in processing human voice speech stimuli: ERP variations in breast and milk formula-fed infants at 3 and 6 months after birth. Dev Neuropsychol. 2007;31(3):279-335. | Group size
1827 | Piwoz, E. G.,Creed de Kanashiro, H.,Lopez de Romana, G. L.,Black, R. E.,Brown, K. H. Feeding practices and growth among low-income Peruvian infants: a comparison of internationally-recommended definitions. Int J Epidemiol. 1996;25(1):103-14. | Independent variable
1828 | Pizarro, F.,Yip, R.,Dallman, P. R.,Olivares, M.,Hertrampf, E.,Walter, T. Iron status with different infant feeding regimens: relevance to screening and prevention of iron deficiency. J Pediatr. 1991;118(5):687-92. | Study design, Independent variable
1829 | Plachta-Danielzik, S.,Kehden, B.,Landsberg, B.,Schaffrath Rosario, A.,Kurth, B. M.,Arnold, C.,Graf, C.,Hense, S.,Ahrens, W.,Muller, M. J. Attributable risks for childhood overweight: evidence for limited effectiveness of prevention. Pediatrics. 2012;130(4):e865-71. | Study design
1830 | Plagemann, A.,Harder, T.,Franke, K.,Kohlhoff, R. Long-term impact of neonatal breast-feeding on body weight and glucose tolerance in children of diabetic mothers. Diabetes Care. 2002;25(1):16-22. | Independent variable
1831 | Plagemann, A.,Harder, T.,Kohlhoff, R.,Fahrenkrog, S.,Rodekamp, E.,Franke, K.,Dudenhausen, J. W. Impact of early neonatal breast-feeding on psychomotor and neuropsychological development in children of diabetic mothers. Diabetes Care. 2005;28(3):573-8. | Independent variable
1832 | Plagemann, A.,Harder, T.,Rodekamp, E.,Kohlhoff, R. Rapid neonatal weight gain increases risk of childhood overweight in offspring of diabetic mothers. J Perinat Med. 2012;40(5):557-63. | Independent variable
1833 | Plenge-Bonig, A.,Soto-Ramirez, N.,Karmaus, W.,Petersen, G.,Davis, S.,Forster, J. Breastfeeding protects against acute gastroenteritis due to rotavirus in infants. Eur J Pediatr. 2010;169(12):1471-6. | Study design, Independent variable
1834 | Plonka, K. A.,Pukallus, M. L.,Barnett, A. G.,Walsh, L. J.,Holcombe, T. F.,Seow, W. K. A longitudinal study comparing mutans streptococci and lactobacilli colonisation in dentate children aged 6 to 24 months. Caries Res. 2012;46(4):385-93. | Included for systematic reviews not completed
1835 | Plonka, K. A.,Pukallus, M. L.,Barnett, A. G.,Walsh, L. J.,Holcombe, T. H.,Seow, W. K. Mutans streptococci and lactobacilli colonization in predentate children from the neonatal period to seven months of age. Caries Res. 2012;46(3):213-20. | Included for systematic reviews not completed
1836 | Podratz, R. O.,Broughton, D. D.,Gustafson, D. H.,Bergstralh, E. J.,Melton, L. J., 3rd. Weight loss and body temperature changes in breast-fed and bottle-fed neonates. Clin Pediatr (Phila). 1986;25(2):73-7. | Included for systematic reviews not completed
1837 | POEMs. Breastfeeding does not decrease risk of asthma and allergy. JAAPA: Journal of the American Academy of Physician Assistants (Haymarket Media, Inc.). 2008;21(1):66-66 1p. | Study design
1838 | Pohlabeln, H.,Muhlenbruch, K.,Jacobs, S.,Bohmann, H. Frequency of allergic diseases in 2-year-old children in relationship to parental history of allergy and breastfeeding. J Investig Allergol Clin Immunol. 2010;20(3):195-200. | Independent variable
1839 | Poikonen, S.,Puumalainen, T. J.,Kautiainen, H.,Palosuo, T.,Reunala, T.,Turjanmaa, K. Sensitization to turnip rape and oilseed rape in children with atopic dermatitis: a case-control study. Pediatr Allergy Immunol. 2008;19(5):408-11. | Independent variable
1840 | Pollock, J. I.. Long-term associations with infant feeding in a clinically advantaged population of babies. Dev Med Child Neurol. 1994;36(5):429-40. | Independent variable
1841 | Pomerance, H. H. Growth in breast-fed children. Hum Biol. 1987;59(4):687-93. | Independent variable
1842 | Porro, E.,Indinnimeo, L.,Antognoni, G.,Midulla, F.,Criscione, S. Early wheezing and breast feeding. J Asthma. 1993;30(1):23-8. | Dependent variable
1843 | Portela, D. S.,Vieira, T. O.,Matos, S. M.,de Oliveira, N. F.,Vieira, G. O. Maternal obesity, environmental factors, cesarean delivery and breastfeeding as determinants of overweight and obesity in children: results from a cohort. BMC Pregnancy Childbirth. 2015;15:94. | Included for systematic reviews not completed
1844 | Portoian-Shuhaiber, S.,Al-Rashied, A. A. Feeding practices and electrolyte disturbances among infants admitted with acute diarrhoea--a survey in Kuwait. J Trop Pediatr. 1986;32(4):168-73. | Study design, Health status
1845 | Potera, Carol. Prolonged Bottle Feeding Raises Childhood Obesity Risk: Weaning around one year is recommended. American Journal of Nursing. 2011;111(8):17-17 1p. | Study design
1846 | Potter, A.,Lumley, J.,Watson, L. The ‘new’ risk factors for SIDS: is there an association with the ethnic and place of birth differences in incidence in Victoria, Australia?. Early Hum Dev. 1996;45(1-2):119-31. | Independent variable, Dependent variable
1847 | Potter, C. M.,Ulijaszek, S. J. Predicting adult obesity from measures in earlier life. J Epidemiol Community Health. 2013;67(12):1032-7. | Study design, Independent variable
1848 | Potur, A. H.,Kalmaz, N. An investigation into feeding errors of 0-4-month-old infants. J Trop Pediatr. 1995;41(2):120-2. | Study design
1849 | Poysa, L. Atopy in children with and without a family history of atopy. II. Skin reactivity. Acta Paediatr Scand. 1989;78(6):902-6. | Independent variable
1850 | Poysa, L.,Korppi, M.,Remes, K.,Juntunen-Backman, K. Atopy in childhood and diet in infancy. A nine-year follow-up study. I. Clinical manifestations. Allergy Proc. 1991;12(2):107-11. | Group size
1851 | Poysa, L.,Korppi, M.,Remes, K.,Juntunen-Backman, K. Predictive value of IgE levels in infancy. Acta Paediatr Scand. 1990;79(10):970-2. | Study design, Dependent variable
1852 | Poysa, L.,Remes, K.,Korppi, M.,Juntunen-Backman, K. Atopy in children with and without a family history of atopy. I. Clinical manifestations, with special reference to diet in infancy. Acta Paediatr Scand. 1989;78(6):896-901. | Group size
1853 | Prado-Montes de Oca, E.,Garcia-Vargas, A.,Lozano-Inocencio, R.,Gallegos-Arreola, M. P.,Sandoval-Ramirez, L.,Davalos-Rodriguez, N. O.,Figuera, L. E. Association of beta-defensin 1 single nucleotide polymorphisms with atopic dermatitis. Int Arch Allergy Immunol. 2007;142(3):211-8. | Study design
1854 | Prado-Montes De Oca, E.,García-Vargas, A.,Lozano-Inocencio, R.,Gallegos-Arreola, M. P.,Sandoval-Ramírez, L.,Dávalos-Rodríguez, N. O.,Figuera, L. E. Association of β-defensin 1 single nucleotide polymorphisms with atopic dermatitis. International Archives of Allergy and Immunology. 2007;142(3):211-218. | Study design
1855 | Prathanee, B.,Purdy, S. C.,Thinkhamrop, B.,Chaimay, B.,Ruangdaraganon, N.,Mo-suwan, L.,Phuphaibul, R. Early language delay and predictive factors in children aged 2 years. J Med Assoc Thai. 2009;92(7):930-8. | Included for systematic reviews not completed
1856 | Pratt, H. F. Breastfeeding and eczema. Early Hum Dev. 1984;9(3):283-90. | Independent variable
1857 | Prentice, P.,Koulman, A.,Matthews, L.,Acerini, C. L.,Ong, K. K.,Dunger, D. B. Lipidomic analyses, breast- and formula-feeding, and growth in infants. J Pediatr. 2015;166(2):276-81 e6. | Included for systematic reviews not completed
1858 | Price, Gareth. A test of temperament. Midwives. 2011;14(4):13-13 1p. | Study design
1859 | Priego, T.,Sanchez, J.,Pico, C.,Ahrens, W.,Bammann, K.,De Henauw, S.,Fraterman, A.,Iacoviello, L.,Lissner, L.,Molnar, D.,Moreno, L. A.,Siani, A.,Tornaritis, M.,Veidebaum, T.,Palou, A. Influence of breastfeeding on blood-cell transcript-based biomarkers of health in children. Pediatr Obes. 2014;9(6):463-70. | Study design, Dependent variable
1860 | Priya, N. Gayathri,Victoria, L. Eilean,Porkodi, A.,Eaton, Linda,Doorenbos, Ardith. Effectiveness of Breastfeeding Empowerment Programme among Primigravidae. Communicating Nursing Research. 2013;46:579-579 1p. | Country
1861 | Procter, S. B.,Holcomb, C. A. Breastfeeding duration and childhood overweight among low-income children in Kansas, 1998-2002. Am J Public Health. 2008;98(1):106-10. | Included for systematic reviews not completed
1862 | Prodam, F.,Roccio, M.,Trovato, L.,Ricotti, R.,Moia, S.,Giglione, E.,Petri, A.,Walker, G. E.,Bellone, S.,Bona, G. Adiponectin oligomers are similarly distributed in adequate-for-gestational-age obese children irrespective of feeding in their first year. Pediatr Res. 2015;77(6):808-13. | Study design
1863 | Project report. Results and policy implications of the cross-national investigation: Rethinking Infant Nutrition Policies under changing Socio-Economic Conditions. Acta Paediatr Scand Suppl. 1984;314:1-61. | Study design, Dependent variable
1864 | Prolonged breast feeding reduces later cardiovascular risk. Arch Dis Child. 2009;94(11):882. | Study design
1865 | Promoting breast-feeding: fewer infections than in bottle-fed babies. Very few contraindications to breast-feeding. Prescrire international. 2009;18(102):178. | Study design
1866 | Protective effect of breast milk against pneumonia is greatest for young infants. Bmj. 1999;318(7194):C. | Study design
1867 | Puccio, G.,Cajozzo, C.,Meli, F.,Rochat, F.,Grathwohl, D.,Steenhout, P. Clinical evaluation of a new starter formula for infants containing live Bifidobacterium longum BL999 and prebiotics. Nutrition. 2007;23(1):1-8. | Independent variable
1868 | Pugh, L. C.,Milligan, R. A. Nursing intervention to increase the duration of breastfeeding. Appl Nurs Res. 1998;11(4):190-4. | Study design, Dependent variable
1869 | Pugh, L. C.,Milligan, R. A.,Frick, K. D.,Spatz, D.,Bronner, Y. Breastfeeding duration, costs, and benefits of a support program for low-income breastfeeding women. Birth. 2002;29(2):95-100. | Group size
1870 | Puig, C.,Sunyer, J.,Garcia-Algar, O.,Munoz, L.,Pacifici, R.,Pichini, S.,Vall, O. Incidence and risk factors of lower respiratory tract illnesses during infancy in a Mediterranean birth cohort. Acta Paediatr. 2008;97(10):1406-11. | Included for systematic reviews not completed
1871 | Pukander J,Luotonen J,Timonen M,Karma P. Risk factors affecting the occurrence of acute otitis media among 2-3-year-old urban children. Acta Otolaryngol. 1985;100:260-5. | Included for systematic reviews not completed
1872 | Pukander, J. Acute otitis media among rural children in Finland. Int J Pediatr Otorhinolaryngol. 1982;4(4):325-32. | Included for systematic reviews not completed
1873 | Pullan, C. R.,Toms, G. L.,Martin, A. J.,Gardner, P. S.,Webb, J. K.,Appleton, D. R. Breast-feeding and respiratory syncytial virus infection. Br Med J. 1980;281(6247):1034-6. | Included for systematic reviews not completed
1874 | Purssell, E. A topic in 10 questions: Gastrointestinal infections from a nutritional perspective. J Fam Health Care. 2012;22(1):28-9. | Study design
1875 | Putet, G.,Labaune, J. M.,Mace, K.,Steenhout, P.,Grathwohl, D.,Raverot, V.,Morel, Y.,Picaud, J. C. Effect of dietary protein on plasma insulin-like growth factor-1, growth, and body composition in healthy term infants: a randomised, double-blind, controlled trial (Early Protein and Obesity in Childhood (EPOCH) study). Br J Nutr. 2015:1-14. | Included for systematic reviews not completed
1876 | Putra, S. T.,Mansyur, M.,Sastroasmoro, S. Effects of duration of breastfeeding during infancy on vascular dysfunction in adolescents. Acta Med Indones. 2015;47(1):24-30. | Study design, Country
1877 | Qudsia, F.,Saboor, M.,Khosa, S. M.,Ayub, Q.,Moinuddin,. Comparative analysis of serum iron, serum ferritin and red cell folate levels among breast fed, fortified milk and cow’s milk fed infants. Pakistan Journal of Medical Sciences. 2015;31(3):706-709. | Country
1878 | Queiroz, V. A.,Assis, A. M.,Pinheiro, S. M.,Ribeiro, H. C., Jr. Predictors of linear growth in the first year of life of a prospective cohort of full term children with normal birth weight. J Pediatr (Rio J). 2012;88(1):79-86. | Independent variable
1879 | Quialey, M. A.,Cumberland, P.,Cowden, J. M.,Rodrigues, L. C. How protective is breast feeding against diarrhoeal disease in infants in 1990s England? A case-control study. Archives of Disease in Childhood. 2006;91(3):245-250. | Included for systematic reviews not completed
1880 | Quigley, M. A.,Hockley, C.,Carson, C.,Kelly, Y.,Renfrew, M. J.,Sacker, A. Breastfeeding is associated with improved child cognitive development: a population-based cohort study. J Pediatr. 2012;160(1):25-32. | Included for systematic reviews not completed
1881 | Quigley, M. A.,Kelly, Y. J.,Sacker, A. Breastfeeding and hospitalization for diarrheal and respiratory infection in the United Kingdom Millennium Cohort Study. Pediatrics. 2007;119(4):e837-42. | Study design
1882 | Quigley, M. A.,Kelly, Y. J.,Sacker, A. Infant feeding, solid foods and hospitalisation in the first 8 months after birth. Arch Dis Child. 2009;94(2):148-50. | Independent variable
1883 | Quinn, P. J.,O’Callaghan, M.,Williams, G. M.,Najman, J. M.,Andersen, M. J.,Bor, W. The effect of breastfeeding on child development at 5 years: a cohort study. J Paediatr Child Health. 2001;37(5):465-9. | Included for systematic reviews not completed
1884 | Quinonez, R.,Santos, R. G.,Wilson, S.,Cross, H. The relationship between child temperament and early childhood caries. Pediatr Dent. 2001;23(1):5-10. | Study design
1885 | Quiroga, M.,Oviedo, P.,Chinen, I.,Pegels, E.,Husulak, E.,Binztein, N.,Rivas, M.,Schiavoni, L.,Vergara, M. Asymptomatic infections by diarrheagenic Escherichia coli in children from Misiones, Argentina, during the first twenty months of their lives. Rev Inst Med Trop Sao Paulo. 2000;42(1):9-15. | Included for systematic reviews not completed
1886 | Qureshi, B.,Morgan, J. B.,Kimer, A. C.,Donaldson, D.,Dickerson, J. W. Feeding practices and birth weights of infants in Southall, Middlesex. J R Soc Health. 1988;108(3):77-80. | Dependent variable
1887 | Rabiei, S. The Association of Nutrition Style through the First 2 Years of Life with Type 1 Diabetes Mellitus and Some of the Other Effective Factors in 2-15 Years Old Children. Iranian Journal of Endocrinology & Metabolism. 2011;13(1):9-113 105p. | Language
1888 | Radlovic, N. P.,Mladenovic, M. M.,Lekovic, Z. M.,Stojsic, Z. M.,Radlovic, V. N. Influence of early feeding practices on celiac disease in infants. Croat Med J. 2010;51(5):417-22. | Independent variable, Health status
1889 | Rady, H. I.,Samir, H.,Tomerak, R.,Gaafar, M. Occult blood in stool in exclusively formula fed infants versus exclusively breast fed infants in the first six months of life. Egyptian Pediatric Association Gazette. 2014;62(1):8-13. | Study design, Country
1890 | Raftowicz-Wójcik, K.,Matthews-Brzozowska, T.,Kawala, B.,Antoszewska, J. The effects of breast feeding on occlusion in primary dentition. Advances in Clinical and Experimental Medicine. 2011;20(3):371-375. | Study design
1891 | Rahman, M.,Roy, S. K.,Ali, M.,Mitra, A. K.,Alam, A. N.,Akbar, M. S. Maternal nutritional status as a determinant of child health. J Trop Pediatr. 1993;39(2):86-8. | Country
1892 | Raiha, N. C.,Fazzolari-Nesci, A.,Boehm, G. Taurine supplementation prevents hyperaminoacidemia in growing term infants fed high-protein cow’s milk formula. Acta Paediatr. 1996;85(12):1403-7. | Group size
1893 | Raiha, N. C.,Fazzolari-Nesci, A.,Cajozzo, C.,Puccio, G.,Monestier, A.,Moro, G.,Minoli, I.,Haschke-Becher, E.,Bachmann, C.,Van’t Hof, M.,Carrie Fassler, A. L.,Haschke, F. Whey predominant, whey modified infant formula with protein/energy ratio of 1.8 g/100 kcal: adequate and safe for term infants from birth to four months. J Pediatr Gastroenterol Nutr. 2002;35(3):275-81. | Independent variable
1894 | Räihä, N.,Fazzolari, A.,Cayozzo, C.,Puccio, G.,Minoli, I.,Moro, G.,Monestier, A.,Haschke-Becher, E.,Carrié, A. L.,Haschke, F. Infant formula with 1.8g Protein/100 Kcal is adequate and safe from birth to 4 months. Revue Medicale Libanaise. 2002;14(1):29-31. | Group size
1895 | Raiha, N.,Minoli, I.,Moro, G. Milk protein intake in the term infant. I. Metabolic responses and effects on growth. Acta Paediatr Scand. 1986;75(6):881-6. | Group size
1896 | Raisler, J.,Alexander, C.,O’Campo, P. Breast-feeding and infant illness: a dose-response relationship?. Am J Public Health. 1999;89(1):25-30. | Study design, Health status
1897 | Ramezani, G. H.,Norozi, A.,Valael, N. The prevalence of nursing caries in 18 to 60 months old children in Qazvin. J Indian Soc Pedod Prev Dent. 2003;21(1):19-26. | Study design
1898 | Ramirez, G. B.,Pagulayan, O.,Akagi, H.,Francisco Rivera, A.,Lee, L. V.,Berroya, A.,Vince Cruz, M. C.,Casintahan, D. Tagum study II: follow-up study at two years of age after prenatal exposure to mercury. Pediatrics. 2003;111(3):e289-95. | Country
1899 | Ramirez-Silva, I.,Rivera, J.,Martorell, R.,Stein, A.,Ramakrishnan, U. Breastfeeding at 3 months is associated with lower risk of adiposity and lipid metabolism alterations at 4 y of age. Annals of nutrition & metabolism. 2013;63:774-5. | Study design
1900 | Ramos, D. E. Breastfeeding: a bridge to addressing disparities in obesity and health. Breastfeed Med. 2012;7(5):354-7. | Study design
1901 | Ramos-Gomez, F. J.,Tomar, S. L.,Ellison, J.,Artiga, N.,Sintes, J.,Vicuna, G. Assessment of early childhood caries and dietary habits in a population of migrant Hispanic children in Stockton, California. ASDC J Dent Child. 1999;66(6):395-403, 366. | Study design
1902 | Rannan-Eliya, R. P.,Hossain, S. M.,Anuranga, C.,Wickramasinghe, R.,Jayatissa, R.,Abeykoon, A. T. Trends and determinants of childhood stunting and underweight in Sri Lanka. Ceylon Med J. 2013;58(1):10-8. | Study design
1903 | Ransome, O. J.,Chalmers, B.,Herman, A. A.,Reinach, S. G. Infant feeding in an urban community. S Afr Med J. 1988;74(8):393-5. | Study design, Country
1904 | Rao, M. R.,Hediger, M. L.,Levine, R. J.,Naficy, A. B.,Vik, T. Effect of breastfeeding on cognitive development of infants born small for gestational age. Acta Paediatr. 2002;91(3):267-74. | Independent variable, Health status
1905 | Rao, S.,Kanade, A. N. Prolonged breast-feeding and malnutrition among rural Indian children below 3 years of age. Eur J Clin Nutr. 1992;46(3):187-95. | Country
1906 | Rao, S.,Rajpathak, V. Breastfeeding and weaning practices in relation to nutritional status of infants. Indian pediatrics. 1992;29(12):1533-1539. | Country
1907 | Rasmussen, K. M.,Kjolhede, C. L. Maternal obesity: a problem for both mother and child. Obesity (Silver Spring). 2008;16(5):929-31. | Study design
1908 | Rassin, D. K.,Raiha, N. C.,Minoli, I.,Moro, G. Taurine and cholesterol supplementation in the term infant: responses of growth and metabolism. JPEN J Parenter Enteral Nutr. 1990;14(4):392-7. | Group size
1909 | Ratageri, V. H.,Kabra, S. K.,Dwivedi, S. N.,Seth, V. Factors associated with severe asthma. Indian Pediatr. 2000;37(10):1072-82. | Country
1910 | Rathnayake, K. M.,Satchithananthan, A.,Mahamithawa, S.,Jayawardena, R. Early life predictors of preschool overweight and obesity: a case-control study in Sri Lanka. BMC Public Health. 2013;13:994. | Study design, Independent variable
1911 | Ravelli, A. C.,van der Meulen, J. H.,Osmond, C.,Barker, D. J.,Bleker, O. P. Infant feeding and adult glucose tolerance, lipid profile, blood pressure, and obesity. Arch Dis Child. 2000;82(3):248-52. | Independent variable
1912 | Rawashdeh, M. O.,Khalil, B.,Raweily, E. Celiac disease in Arabs. J Pediatr Gastroenterol Nutr. 1996;23(4):415-8. | Study design, Independent variable, Health status
1913 | Ray G. Infant feeding. Psychology of choice. Nurs Mirror. 1985;160:25-8. | Study design
1914 | RC currents. Children breast-fed by asthmatic mothers at risk, says study. AARC Times. 2001;25(4):70-70 1p. | Study design
1915 | Reading, R. Effects of prolonged and exclusive breastfeeding on child behavior and maternal adjustment: evidence from a large, randomized trial..Kramer MS, Fombonne E, Igumnov S, Vanilovich L, Matush L, Mironova E, Bogdanovich N, Tremblay RE, Chalmers B, Zhang X & Platt RW for the PROBIT study group (2008) Pediatrics, 121, E435-40. Child: Care, Health & Development. 2008;34(4):547-547 1p. | Study design
1916 | Rebhan, B.,Kohlhuber, M.,Schwegler, U.,Fromme, H.,Abou-Dakn, M.,Koletzko, B. V. Breastfeeding duration and exclusivity associated with infants’ health and growth: data from a prospective cohort study in Bavaria, Germany. Acta Paediatr. 2009;98(6):974-80. | Included for systematic reviews not completed
1917 | Regnault, N.,Botton, J.,Blanc, L.,Hankard, R.,Forhan, A.,Goua, V.,Thiebaugeorges, O.,Kaminski, M.,Heude, B.,Charles, M. A. Determinants of neonatal weight loss in term-infants: specific association with pre-pregnancy maternal body mass index and infant feeding mode. Arch Dis Child Fetal Neonatal Ed. 2011;96(3):F217-22. | Included for systematic reviews not completed
1918 | Regnault, N.,Botton, J.,Forhan, A.,Hankard, R.,Thiebaugeorges, O.,Hillier, T. A.,Kaminski, M.,Heude, B.,Charles, M. A. Determinants of early ponderal and statural growth in full-term infants in the EDEN mother-child cohort study. Am J Clin Nutr. 2010;92(3):594-602. | Included for systematic reviews not completed
1919 | Regnault,N,Botton,J,Forhan,A,Hankard,R,Thiebaugeorges,O,Hillier,T, A.,Kaminski,M,Heude,B,Charles,M, A. Determinants of early ponderal and statural growth in full-term infants in the EDEN mother-child cohort study. Am J Clin Nutr. 2010;92(3):594-602. | Duplicate
1920 | Reid, A. Infant feeding and post-neonatal mortality in Derbyshire, England, in the early twentieth century. Popul Stud (Camb). 2002;56(2):151-66. | Dependent variable
1921 | Renn, M. Baby milk: is breast second best?. Nurs Times. 1987;83(6):19-20. | Study design
1922 | Rennie, A. M.,Rowand, J. The beautiful game and breastfeeding. Pract Midwife. 2012;15(9):46. | Study design
1923 | Renz, H.,Brehler, C.,Petzoldt, S.,Prinz, H.,Rieger, C. H. Breast feeding modifies production of SIgA cow’s milk-antibodies in infants. Acta Paediatr Scand. 1991;80(2):149-54. | Dependent variable
1924 | Reyes Romagosa, D. E.,Paneque Gamboa, M. R.,Almeida Muniz, Y.,Quesada Oliva, L. M.,Escalona Oliva, D.,Torres Naranjo, S. Risk factors associated with deforming oral habits in children aged 5 to 11: a case-control study. Medwave. 2014;14(2):e5927. | Language
1925 | Reyes, H.,Perez-Cuevas, R.,Salmeron, J.,Tome, P.,Guiscafre, H.,Gutierrez, G. Infant mortality due to acute respiratory infections: the influence of primary care processes. Health Policy Plan. 1997;12(3):214-23. | Independent variable, Health status
1926 | Reyes, H.,Perez-Cuevas, R.,Sandoval, A.,Castillo, R.,Santos, J. I.,Doubova, S. V.,Gutierrez, G. The family as a determinant of stunting in children living in conditions of extreme poverty: a case-control study. BMC Public Health. 2004;4:57. | Included for systematic reviews not completed
1927 | Reyes, M.,Hoyos, V.,Martinez, S. M.,Lozoff, B.,Castillo, M.,Burrows, R.,Blanco, E.,Gahagan, S. Satiety responsiveness and eating behavior among Chilean adolescents and the role of breastfeeding. Int J Obes (Lond). 2014;38(4):552-7. | Independent variable
1928 | Reynolds, D.,Hennessy, E.,Polek, E. Is breastfeeding in infancy predictive of child mental well-being and protective against obesity at 9 years of age?. Child Care Health Dev. 2014;40(6):882-90. | Study design
1929 | Rhodes C. The benefits of breast-feeding. J Pract Nurs. 1982;32:19-21, 54-5. | Study design
1930 | Ribadeau-Dumas, B. Human milk. Endeavour. 1983;7(2):80-7. | Study design
1931 | Ribas-Fito, N.,Cardo, E.,Sala, M.,Eulalia de Muga, M.,Mazon, C.,Verdu, A.,Kogevinas, M.,Grimalt, J. O.,Sunyer, J. Breastfeeding, exposure to organochlorine compounds, and neurodevelopment in infants. Pediatrics. 2003;111(5 Pt 1):e580-5. | Group size
1932 | Ribas-Fito, N.,Julvez, J.,Torrent, M.,Grimalt, J. O.,Sunyer, J. Beneficial effects of breastfeeding on cognition regardless of DDT concentrations at birth. Am J Epidemiol. 2007;166(10):1198-202. | Independent variable
1933 | Ricco, R. G.,Nogueira-de-Almeida, C. A.,Del Ciampo, L. A.,Daneluzzi, J. C.,Ferlin, M. L.,Muccillo, G. Growth of exclusively breast-fed infants from a poor urban population. Arch Latinoam Nutr. 2001;51(2):122-6. | Included for systematic reviews not completed
1934 | Richards, M.,Hardy, R.,Wadsworth, M. E. Long-term effects of breast-feeding in a national birth cohort: educational attainment and midlife cognitive function. Public Health Nutr. 2002;5(5):631-5. | Included for systematic reviews not completed
1935 | Richards, M.,Wadsworth, M.,Rahimi-Foroushani, A.,Hardy, R.,Kuh, D.,Paul, A. Infant nutrition and cognitive development in the first offspring of a national UK birth cohort. Dev Med Child Neurol. 1998;40(3):163-7. | Independent variable
1936 | Richardson, B. D.,Cleaton-Jones, P. E.,McInnes, P. M.,Rantsho, J. M. Infant feeding practices and nursing bottle caries. ASDC J Dent Child. 1981;48(6):423-9. | Study design, Country
1937 | Rich-Edwards, J. W.,Stampfer, M. J.,Manson, J. E.,Rosner, B.,Hu, F. B.,Michels, K. B.,Willett, W. C. Breastfeeding during infancy and the risk of cardiovascular disease in adulthood. Epidemiology. 2004;15(5):550-6. | Independent variable
1938 | Richman, D.,Dixon, S. Comparative study of Cambodian, Hmong, and Caucasian infant and maternal perinatal profiles. J Nurse Midwifery. 1985;30(6):313-9. | Independent variable
1939 | Rigby, A. S.,Sanderson, C.,Desforges, M. F.,Lindsay, G.,Hall, D. M. The infant index: a new outcome measure for pre-school children’s services. J Public Health Med. 1999;21(2):172-8. | Included for systematic reviews not completed
1940 | Rigo, J.,Salle, B. L.,Cavero, E.,Richard, P.,Putet, G.,Senterre, J. Plasma amino acid and protein concentrations in infants fed human milk or a whey protein hydrolysate formula during the first month of life. Acta Paediatr. 1994;83(2):127-31. | Group size
1941 | Rigo, J.,Salle, B. L.,Picaud, J. C.,Putet, G.,Senterre, J. Nutritional evaluation of protein hydrolysate formulas. Eur J Clin Nutr. 1995;49 Suppl 1:S26-38. | Group size
1942 | Riordan, J.,Countryman, B. A. Basics of breastfeeding. Part IV: Preparation for breastfeeding and early optimal functioning. JOGN Nurs. 1980;9(5):277-83. | Study design, Dependent variable
1943 | Rios-Castillo, I.,Cerezo, S.,Corvalan, C.,Martinez, M.,Kain, J. Risk factors during the prenatal period and the first year of life associated with overweight in 7-year-old low-income Chilean children. Matern Child Nutr. 2015;11(4):595-605. | Included for systematic reviews not completed
1944 | Riva, V.,Battaglia, M.,Nobile, M.,Cattaneo, F.,Lazazzera, C.,Mascheretti, S.,Giorda, R.,Merette, C.,Emond, C.,Maziade, M.,Marino, C. GRIN2B predicts attention problems among disadvantaged children. Eur Child Adolesc Psychiatry. 2015;24(7):827-36. | Study design
1945 | Roberts AK. Prospects for further approximation of infant formulae to human milk. Midwife Health Visit Community Nurse. 1987;23:140-6. | Study design, Dependent variable
1946 | Roberts, C. C.,Chan, G. M.,Folland, D.,Rayburn, C.,Jackson, R. Adequate bone mineralization in breast-fed infants. J Pediatr. 1981;99(2):192-6. | Group size
1947 | Roberts, D. W. Growth of breast fed and bottle fed infants. N Z Med J. 1980;92(664):45-6. | Included for systematic reviews not completed
1948 | Roberts, G. J. Is breast feeding a possible cause of dental caries?. J Dent. 1982;10(4):346-52. | Study design
1949 | Robinson, M.,Oddy, W. H.,Li, J.,Kendall, G. E.,de Klerk, N. H.,Silburn, S. R.,Zubrick, S. R.,Newnham, J. P.,Stanley, F. J.,Mattes, E. Pre- and postnatal influences on preschool mental health: a large-scale cohort study. J Child Psychol Psychiatry. 2008;49(10):1118-28. | Included for systematic reviews not completed
1950 | Robinson, S. M.,Crozier, S. R.,Harvey, N. C.,Barton, B. D.,Law, C. M.,Godfrey, K. M.,Cooper, C.,Inskip, H. M. Modifiable early-life risk factors for childhood adiposity and overweight: an analysis of their combined impact and potential for prevention. Am J Clin Nutr. 2015;101(2):368-75. | Included for systematic reviews not completed
1951 | Robinson, S. M.,Marriott, L. D.,Crozier, S. R.,Harvey, N. C.,Gale, C. R.,Inskip, H. M.,Baird, J.,Law, C. M.,Godfrey, K. M.,Cooper, C. Variations in infant feeding practice are associated with body composition in childhood: a prospective cohort study. J Clin Endocrinol Metab. 2009;94(8):2799-805. | Independent variable
1952 | Rochat, F.,Cherbut, C.,Barclay, D.,Puccio, G.,Fazzolari-Nesci, A.,Grathwohl, D.,Haschke, F. A whey-predominant formula induces fecal microbiota similar to that found in breast-fed infants. Nutrition Research. 2007;27(12):735-740. | Dependent variable
1953 | Roche, A. F.,Guo, S.,Siervogel, R. M.,Khamis, H. J.,Chandra, R. K. Growth comparison of breast-fed and formula-fed infants. Can J Public Health. 1993;84(2):132-5. | Included for systematic reviews not completed
1954 | Rodekamp, E.,Harder, T.,Kohlhoff, R.,Dudenhausen, J. W.,Plagemann, A. Impact of breast-feeding on psychomotor and neuropsychological development in children of diabetic mothers: role of the late neonatal period. J Perinat Med. 2006;34(6):490-6. | Independent variable
1955 | Rodriguez Martinez, C.,Sossa, M.,Goss, C. H. Factors associated with severe disease in a population of asthmatic children of Bogota, Colombia. J Asthma. 2008;45(2):141-7. | Study design
1956 | Rodriguez-Lopez, M.,Osorio, L.,Acosta-Rojas, R.,Figueras, J.,Cruz-Lemini, M.,Figueras, F.,Bijnens, B.,Gratacos, E.,Crispi, F. Influence of breastfeeding and postnatal nutrition on cardiovascular remodeling induced by fetal growth restriction. Pediatr Res. 2015. | Independent variable, Health status
1957 | Roelants, M.,Hauspie, R.,Hoppenbrouwers, K. Breastfeeding, growth and growth standards: Performance of the WHO growth standards for monitoring growth of Belgian children. Ann Hum Biol. 2010;37(1):2-9. | Independent variable
1958 | Rogan, W. J.,Gladen, B. C. Breast-feeding and cognitive development. Early Hum Dev. 1993;31(3):181-93. | Included for systematic reviews not completed
1959 | Rolland-Cachera, M. F.,Peneau, S. Assessment of growth: variations according to references and growth parameters used. Am J Clin Nutr. 2011;94(6 Suppl):1794S-1798S. | Study design
1960 | Romano, A. M. Longer duration of breastfeeding is associated with lower risk of type-2 diabetes (abst; commentary). Journal of Perinatal Education. 2006;15(2):54-55 2p. | Study design
1961 | Romero, C. C.,Scavone Jr, H.,Garib, D. G.,Cotrim-Ferreira, F. A.,Ferreira, I. R. Breastfeeding and non-nutritive sucking patterns related to the prevalence of anterior open bite in primary dentition. Journal of Applied Oral Science. 2011;19(2):161-168. | Study design
1962 | Romieu, I.,Werneck, G.,Ruiz Velasco, S.,White, M.,Hernandez, M. Breastfeeding and asthma among Brazilian children. J Asthma. 2000;37(7):575-83. | Study design
1963 | Rona, R. J.,Smeeton, N. C.,Bustos, P.,Amiga, H.,Diaz, P. V. The early origins hypothesis with an emphasis on growth rate in the first year of life and asthma: A prospective study in Chile. Thorax. 2005;60(7):549-554. | Dependent variable
1964 | Rose, C. M.,Savage, J. S.,Birch, L. L. Patterns of early dietary exposures have implications for maternal and child weight outcomes. Obesity (Silver Spring). 2016;24(2):430-8. | Study design, Independent variable
1965 | Rosenbauer, J.,Herzig, P.,Kaiser, P.,Giani, G. Early nutrition and risk of Type 1 diabetes mellitus--a nationwide case-control study in preschool children. Exp Clin Endocrinol Diabetes. 2007;115(8):502-8. | Redundant data
1966 | Rosenberg, M. Breast-feeding and infant mortality in Norway 1860-1930. J Biosoc Sci. 1989;21(3):335-48. | Independent variable
1967 | Rosenblatt, A.,Zarzar, P. The prevalence of early childhood caries in 12- to 36-month-old children in Recife, Brazil. ASDC J Dent Child. 2002;69(3):319-24, 236. | Study design
1968 | Rosenblatt, W. H.,Brown, E. G. The nutritional status of breast-fed infants in a rural Peruvian community. J Trop Pediatr. 1988;34(6):319-22. | Study design
1969 | Rossiter, J. C. Breast-feeding, the better option: getting the message across. World Health Forum. 1993;14(3):316-8. | Study design
1970 | Rossiter, M. D.,Colapinto, C. K.,Khan, M. K.,McIsaac, J. L.,Williams, P. L.,Kirk, S. F.,Veugelers, P. J. Breast, Formula and Combination Feeding in Relation to Childhood Obesity in Nova Scotia, Canada. Matern Child Health J. 2015;19(9):2048-56. | Study design
1971 | Rossiter, M. D.,Evers, S. E. Infant feeding practices and children’s weight status. Can J Diet Pract Res. 2013;74(3):107-13. | Independent variable, Dependent variable
1972 | Roszkowska, R.,Taranta-Janusz, K.,Tenderenda-Banasiuk, E.,Wasilewska, A. Increased circulating inflammatory markers may indicate that formula-fed children are at risk of atherosclerosis. Acta Paediatr. 2014;103(8):e354-8. | Study design, Dependent variable
1973 | Roszkowska, R.,Taranta-Janusz, K.,Tenderenda-Banasiuk, E.,Wasilewska, A. The effects of breastfeeding on serum asymmetric dimethylarginine levels and body composition in children. Breastfeed Med. 2015;10:38-44. | Study design
1974 | Rousseau, E. H.,Lescop, J. N.,Fontaine, S.,Lambert, J.,Roy, C. C. Influence of cultural and environmental factors on breast-feeding. Can Med Assoc J. 1982;127(8):701-4. | Dependent variable
1975 | Routi, T.,Ronnemaa, T.,Viikari, J. S.,Leino, A.,Valimaki, I. A.,Simell, O. G. Tracking of serum lipoprotein (a) concentration and its contribution to serum cholesterol values in children from 7 to 36 months of age in the STRIP Baby Study. Special Turku Coronary Risk Factor Intervention Project for Babies. Ann Med. 1997;29(6):541-7. | Independent variable, Dependent variable
1976 | Rowland, M. G. The “why” and “when” of introducing food to infants: growth in young breast-fed infants and some nutritional implications. Am J Clin Nutr. 1985;41(2 Suppl):459-63. | Study design
1977 | Rowntree, S.,Cogswell, J. J.,Platts-Mills, T. A.,Mitchell, E. B. Development of IgE and IgG antibodies to food and inhalant allergens in children at risk of allergic disease. Arch Dis Child. 1985;60(8):727-35. | Dependent variable
1978 | Rubin, D. H.,Leventhal, J. M.,Krasilnikoff, P. A.,Kuo, H. S.,Jekel, J. F.,Weile, B.,Levee, A.,Kurzon, M.,Berget, A. Relationship between infant feeding and infectious illness: a prospective study of infants during the first year of life. Pediatrics. 1990;85(4):464-71. | Independent variable
1979 | Rudant, J.,Lightfoot, T.,Urayama, K. Y.,Petridou, E.,Dockerty, J. D.,Magnani, C.,Milne, E.,Spector, L. G.,Ashton, L. J.,Dessypris, N.,Kang, A. Y.,Miller, M.,Rondelli, R.,Simpson, J.,Stiakaki, E.,Orsi, L.,Roman, E.,Metayer, C.,Infante-Rivard, C.,Clavel, J. Childhood acute lymphoblastic leukemia and indicators of early immune stimulation: A childhood leukemia international consortium study. American Journal of Epidemiology. 2015;181(8):549-562. | Study design
1980 | Rudant, J.,Orsi, L.,Bonaventure, A.,Goujon-Bellec, S.,Baruchel, A.,Petit, A.,Bertrand, Y.,Nelken, B.,Pasquet, M.,Michel, G.,Saumet, L.,Chastagner, P.,Ducassou, S.,Reguerre, Y.,Hemon, D.,Clavel, J. ARID5B, IKZF1 and non-genetic factors in the etiology of childhood acute lymphoblastic leukemia: the ESCALE study. PLoS One. 2015;10(3):e0121348. | Independent variable, Redundant data
1981 | Rudnicka, A. R.,Owen, C. G.,Strachan, D. P. The effect of breastfeeding on cardiorespiratory risk factors in adult life. Pediatrics. 2007;119(5):e1107-15. | Independent variable
1982 | Rudzeviciene, O.,Narkeviciute, I.,Eidukevicius, R. Lactose malabsorption in young Lithuanian children with atopic dermatitis. Acta Paediatr. 2004;93(4):482-6. | Independent variable
1983 | Ruijsbroek, A.,Wijga, A. H.,Kerkhof, M.,Koppelman, G. H.,Smit, H. A.,Droomers, M.. The development of socio-economic health differences in childhood: results of the Dutch longitudinal PIAMA birth cohort. BMC Public Health. 2011;11(#issue#):225. | Included for systematic reviews not completed
1984 | Ruiz-Charles, M. G.,Castillo-Rendón, R.,Bermúdez-Felizardo, F. Risk factors associated to bronchiolitis in infants less than two years of age. Revista de Investigacion Clinica. 2002;54(2):125-132. | Language
1985 | Ruiz-Palacios, G. M.,Calva, J. J.,Pickering, L. K.,Lopez-Vidal, Y.,Volkow, P.,Pezzarossi, H.,West, M. S. Protection of breast-fed infants against Campylobacter diarrhea by antibodies in human milk. J Pediatr. 1990;116(5):707-13. | Group size
1986 | Rullo, V. E.,Arruda, L. K.,Cardoso, M. R.,Valente, V.,Zampolo, A. S.,Nobrega, F.,Naspitz, C. K.,Sole, D. Respiratory infection, exposure to mouse allergen and breastfeeding: role in recurrent wheezing in early life. Int Arch Allergy Immunol. 2009;150(2):172-8. | Independent variable
1987 | Rusconi, F.,Galassi, C.,Corbo, G. M.,Forastiere, F.,Biggeri, A.,Ciccone, G.,Renzoni, E.,Camerlengo, A.,Bugiani, M.,Dalmasso, P.,Faggiano, F.,Volante, T. F.,Magnani, C.,Natale, P.,Piccioni, P.,Bisanti, L.,Gianelle, V.,Sideri, S.,Piffer, S.,Filippetti, F.,Nava, E.,Biocca, M.,Canossa, E.,Cavalchi, B.,Cervino, D.,Cattani, S.,De’Munari, E.,Deserti, M.,Ferro, S.,Fortezza, F.,Frigo, F.,Martini, M.,Mazzali, P.,Paterlini, L.,Sogni, R.,Zanini, M.,Romagna, E.,Chellini, E.,Agati, L.,Barletta, E.,Bini, G.,Bini, M.,Chetoni, L.,Grechi, D.,Costantini, A. S.,Sestini, P.,Viegi, G.,Agabiti, N.,Dell’Orco, V.,Mallone, S.,Micera, C.,Palermo, P.,Pallotti, G.,Piras, C.,Pistelli, R.,Salera, E.,Argentini, D.,Chiarucci, G. Risk factors for early, persistent, and late-onset wheezing in young children. American Journal of Respiratory and Critical Care Medicine. 1999;160(5 I):1617-1622. | Study design
1988 | Rush, E. C.,Paterson, J.,Obolonkin, V. V.,Puniani, K. Application of the 2006 WHO growth standard from birth to 4 years to Pacific Island children. Int J Obes (Lond). 2008;32(3):567-72. | Independent variable
1989 | Rush, E.,Gao, W.,Funaki-Tahifote, M.,Ngamata, R.,Matenga-Smith, T.,Cassidy, M.,Paterson, J. Birth weight and growth trajectory to six years in Pacific children. Int J Pediatr Obes. 2010;5(2):192-9. | Included for systematic reviews not completed
1990 | Russo, R. M.,Patel, R.,Laude, T. A.,Rajkumar, S. V.,Gururaj, V. J. Infant feeding practices by ethno-cultural grouping. J Med Soc N J. 1981;78(11):737-40. | Study design, Dependent variable
1991 | Rutishauser, I. H.,McKay, H. M.,Wahlqvist, M. L. Does breast feeding have nutritional advantages over bottle feeding?. Aust Fam Physician. 1982;11(4):249-50, 252-3, 255-6. | Study design
1992 | Ruuska, T. Occurrence of acute diarrhea in atopic and nonatopic infants: the role of prolonged breast-feeding. J Pediatr Gastroenterol Nutr. 1992;14(1):27-33. | Included for systematic reviews not completed
1993 | Ruuska, T.,Vesikari, T. A prospective study of acute diarrhoea in Finnish children from birth to 2 1/2 years of age. Acta Paediatr Scand. 1991;80(5):500-7. | Group size
1994 | Ruys, J. H.,de Jonge, G. A.,Brand, R.,Engelberts, A. C.,Semmekrot, B. A. Bed-sharing in the first four months of life: a risk factor for sudden infant death. Acta Paediatr. 2007;96(10):1399-403. | Study design
1995 | Rylander, E.,Pershagen, G.,Eriksson, M.,Nordvall, L. Parental smoking and other risk factors for wheezing bronchitis in children. Eur J Epidemiol. 1993;9(5):517-26. | Independent variable
1996 | Rzehak, P.,Sausenthaler, S.,Koletzko, S.,Bauer, C. P.,Schaaf, B.,von Berg, A.,Berdel, D.,Borte, M.,Herbarth, O.,Kramer, U.,Fenske, N.,Wichmann, H. E.,Heinrich, J. Period-specific growth, overweight and modification by breastfeeding in the GINI and LISA birth cohorts up to age 6 years. Eur J Epidemiol. 2009;24(8):449-67. | Independent variable
1997 | Rzehak, P.,Sausenthaler, S.,Koletzko, S.,Reinhardt, D.,von Berg, A.,Kramer, U.,Berdel, D.,Bollrath, C.,Grubl, A.,Bauer, C. P.,Wichmann, H. E.,Heinrich, J. Short- and long-term effects of feeding hydrolyzed protein infant formulas on growth at < or = 6 y of age: results from the German Infant Nutritional Intervention Study. Am J Clin Nutr. 2009;89(6):1846-56. | Independent variable
1998 | Saarinen, K. M.,Juntunen-Backman, K.,Jarvenpaa, A. L.,Klemetti, P.,Kuitunen, P.,Lope, L.,Renlund, M.,Siivola, M.,Vaarala, O.,Savilahti, E. Breast-feeding and the development of cows’ milk protein allergy. Adv Exp Med Biol. 2000;478:121-30. | Peer review
1999 | Saarinen, K. M.,Juntunen-Backman, K.,Jarvenpaa, A. L.,Kuitunen, P.,Lope, L.,Renlund, M.,Siivola, M.,Savilahti, E. Supplementary feeding in maternity hospitals and the risk of cow’s milk allergy: A prospective study of 6209 infants. J Allergy Clin Immunol. 1999;104(2 Pt 1):457-61. | Independent variable
2000 | Saarinen, K. M.,Savilahti, E. Infant feeding patterns affect the subsequent immunological features in cow’s milk allergy. Clin Exp Allergy. 2000;30(3):400-6. | Dependent variable, Health status
2001 | Saarinen, U. M. Prolonged breast feeding as prophylaxis for recurrent otitis media. Acta Paediatr Scand. 1982;71(4):567-71. | Independent variable
2002 | Saarinen, U. M.,Kajosaari, M. Breastfeeding as prophylaxis against atopic disease: prospective follow-up study until 17 years old. Lancet. 1995;346(8982):1065-9. | Independent variable
2003 | Saarinen, U. M.,Kajosaari, M.,Backman, A. Birch pollen allergy in children. Role of milk feeding during the first birch season of life. Allergy. 1982;37(5):345-50. | Dependent variable
2004 | Sabanayagam, C.,Shankar, A.,Chong, Y. S.,Wong, T. Y.,Saw, S. M. Breast-feeding and overweight in Singapore school children. Pediatr Int. 2009;51(5):650-6. | Study design
2005 | Sabuncuoglu, O.,Orengul, C.,Bikmazer, A.,Kaynar, S. Y. Breastfeeding and parafunctional oral habits in children with and without attention-deficit/hyperactivity disorder. Breastfeed Med. 2014;9(5):244-50. | Included for systematic reviews not completed
2006 | Sacker, A.,Kelly, Y.,Iacovou, M.,Cable, N.,Bartley, M. Breast feeding and intergenerational social mobility: what are the mechanisms?. Arch Dis Child. 2013;98(9):666-71. | Independent variable, Dependent variable
2007 | Sacker, A.,Quigley, M. A.,Kelly, Y. J. Breastfeeding and developmental delay: findings from the millennium cohort study. Pediatrics. 2006;118(3):e682-9. | Study design
2008 | Sadeharju, K.,Knip, M.,Virtanen, S. M.,Savilahti, E.,Tauriainen, S.,Koskela, P.,Akerblom, H. K.,Hyoty, H. Maternal antibodies in breast milk protect the child from enterovirus infections. Pediatrics. 2007;119(5):941-6. | Included for systematic reviews not completed
2009 | Saeed, M.,Waseem, Q.,Ali Shair, Q.,Omonogun, B. A.,Al Husein, A. Vitamin D deficiency rickets in Maternity and Children’s Hospital, Najran, Saudi Arabia. Pakistan Paediatric Journal. 2008;32(3):145-148. | No full text
2010 | Sahakyan, A.,Armenian, H. K.,Breitscheidel, L.,Thompson, M. E.,Enokyan, G. Feeding practices of babies and the development of atopic dermatitis in children after 12 months of age in Armenia: Is there a signal?. European Journal of Epidemiology. 2006;21(9):723-725. | Independent variable
2011 | Sahin, F.,Camurdan, A. D.,Camurdan, M. O.,Olmez, A.,Oznurhan, F.,Beyazova, U. Factors affecting the timing of teething in healthy Turkish infants: a prospective cohort study. Int J Paediatr Dent. 2008;18(4):262-6. | Independent variable, Dependent variable
2012 | Sajjad, A.,Tharner, A.,Kiefte-de Jong, J. C.,Jaddoe, V. V.,Hofman, A.,Verhulst, F. C.,Franco, O. H.,Tiemeier, H.,Roza, S. J. Breastfeeding duration and non-verbal IQ in children. J Epidemiol Community Health. 2015;69(8):775-81. | Included for systematic reviews not completed
2013 | Saki Malehi, A.,Hajizadeh, E.,Ahmadi, K.,Kholdi, N. Modeling the recurrent failure to thrive in less than two-year children: recurrent events survival analysis. J Res Health Sci. 2014;14(1):96-9. | Included for systematic reviews not completed
2014 | Salah, M.,Abdel-Aziz, M.,Al-Farok, A.,Jebrini, A. Recurrent acute otitis media in infants: analysis of risk factors. Int J Pediatr Otorhinolaryngol. 2013;77(10):1665-9. | Non-human, Health status
2015 | Salariya, E. M. Breast versus bottle feeding. Nutr Health. 1993;9(1):33-6. | Study design
2016 | Salariya, E. M.,Easton, P. M.,Cater, J. I. Early and often for best results. RCT on breast feeding. Nursing mirror. 1979;148:15-7. | Dependent variable
2017 | Salariya, E. M.,Robertson, C. M. Relationships between baby feeding types and patterns, gut transit time of meconium and the incidence of neonatal jaundice. Midwifery. 1993;9(4):235-42. | Included for systematic reviews not completed
2018 | Salazar, J. C.,Daly, K. A.,Giebink, G. S.,Lindgren, B. R.,Liebeler, C. L.,Meland, M.,Le, C. T. Low cord blood pneumococcal immunoglobulin G (IgG) antibodies predict early onset acute otitis media in infancy. Am J Epidemiol. 1997;145(11):1048-56. | Independent variable
2019 | Salim, S.,Farquharson, J.,Arneil, G. C.,Cockburn, F.,Forbes, G. I.,Logan, R. W.,Sherlock, J. C.,Wilson, T. S. Dietary copper intake in artificially fed infants. Arch Dis Child. 1986;61(11):1068-75. | Included for systematic reviews not completed
2020 | Salmenpera, L.,Perheentupa, J.,Siimes, M. A. Exclusively breast-fed healthy infants grow slower than reference infants. Pediatr Res. 1985;19(3):307-12. | Independent variable
2021 | Salmenpera, L.,Perheentupa, J.,Siimes, M. A.,Adrian, T. E.,Bloom, S. R.,Aynsley-Green, A. Effects of feeding regimen on blood glucose levels and plasma concentrations of pancreatic hormones and gut regulatory peptides at 9 months of age: comparison between infants fed with milk formula and infants exclusively breast-fed from birth. J Pediatr Gastroenterol Nutr. 1988;7(5):651-6. | Group size
2022 | Salmon, T. G., Jr. Early childhood caries: a private practitioner’s perspective. Pediatr Dent. 1997;19(1):63-4. | Study design
2023 | Salo, P.,Viikari, J.,Hamalainen, M.,Lapinleimu, H.,Routi, T.,Ronnemaa, T.,Seppanen, R.,Jokinen, E.,Valimaki, I.,Simell, O. Serum cholesterol ester fatty acids in 7- and 13-month-old children in a prospective randomized trial of a low-saturated fat, low-cholesterol diet: the STRIP baby project. Special Turku coronary Risk factor Intervention Project for children. Acta Paediatr. 1999;88(5):505-12. | Independent variable
2024 | Salsberry, P. J.,Reagan, P. B. Dynamics of early childhood overweight. Pediatrics. 2005;116(6):1329-38. | Included for systematic reviews not completed
2025 | Salsberry, P. J.,Reagan, P. B. Taking the long view: the prenatal environment and early adolescent overweight. Res Nurs Health. 2007;30(3):297-307. | Included for systematic reviews not completed
2026 | Salvioli, G. P.,Faldella, G.,Alessandroni, R.,Lanari, M.,Di Turi, R. P. Iron nutrition and iron status changes in Italian infants in the last decade. Ann Ist Super Sanita. 1995;31(4):455-9. | Study design
2027 | Samarakkody, D.,Fernando, D.,McClure, R.,Perera, H.,De Silva, H. Prevalence of externalizing behavior problems in Sri Lankan preschool children: birth, childhood, and sociodemographic risk factors. Soc Psychiatry Psychiatr Epidemiol. 2012;47(5):757-62. | Study design
2028 | Sanchez-Molins, M.,Grau Carbo, J.,Lischeid Gaig, C.,Ustrell Torrent, J. M. Comparative study of the craniofacial growth depending on the type of lactation received. Eur J Paediatr Dent. 2010;11(2):87-92. | Independent variable
2029 | Sánchez-Uribe, E.,Esparza-Aguilar, M.,Gastañaduy, P. A.,Desai, R.,Patel, M.,Richardson, V. Risk factors associated with rotavirus gastroenteritis during a community outbreak in Chiapas, Mexico during the postvaccination Era. Journal of the Pediatric Infectious Diseases Society. 2013;2(1):15-20. | Independent variable
2030 | Sanchez-Valverde, F.,Gil, F.,Martinez, D.,Fernandez, B.,Aznal, E.,Oscoz, M.,Olivera, J. E. The impact of caesarean delivery and type of feeding on cow’s milk allergy in infants and subsequent development of allergic march in childhood. Allergy. 2009;64(6):884-9. | Health status
2031 | Sandstrom, O.,Lonnerdal, B.,Graverholt, G.,Hernell, O. Effects of alpha-lactalbumin-enriched formula containing different concentrations of glycomacropeptide on infant nutrition. Am J Clin Nutr. 2008;87(4):921-8. | Group size
2032 | Sanger, R. G.,Bystrom, E. B. Breast feeding: does it affect oral facial growth?. Dent Hyg (Chic). 1982;56(6):44-7. | Study design
2033 | Sanin, L. H.,Gonzalez-Cossio, T.,Romieu, I.,Peterson, K. E.,Ruiz, S.,Palazuelos, E.,Hernandez-Avila, M.,Hu, H. Effect of maternal lead burden on infant weight and weight gain at one month of age among breastfed infants. Pediatrics. 2001;107(5):1016-23. | Study design
2034 | Santorelli, G.,Fairley, L.,Petherick, E. S.,Cabieses, B.,Sahota, P. Ethnic differences in infant feeding practices and their relationship with BMI at 3 years of age - results from the Born in Bradford birth cohort study. Br J Nutr. 2014;111(10):1891-7. | Included for systematic reviews not completed
2035 | Santos, C. A.,Strina, A.,Amorim, L. D.,Genser, B.,Assis, A. M.,Prado, M. S.,Barreto, M. L. Individual and contextual determinants of the duration of diarrhoeal episodes in preschool children: a longitudinal study in an urban setting. Epidemiol Infect. 2012;140(4):689-96. | Health status
2036 | Santos, I. S.,Matijasevich, A.,Assuncao, M. C.,Valle, N. C.,Horta, B. L.,Goncalves, H. D.,Gigante, D. P.,Martines, J. C.,Pelto, G.,Victora, C. G. Promotion of Weight Gain in Early Childhood Does Not Increase Metabolic Risk in Adolescents: A 15-Year Follow-Up of a Cluster-Randomized Controlled Trial. J Nutr. 2015;145(12):2749-55. | Independent variable
2037 | Santos, I. S.,Matijasevich, A.,Barros, A. J.,Albernaz, E. P.,Domingues, M. R.,Valle, N. C.,Malta, D. C.,Gorgot, L. R.,Barros, F. C. Avoidable deaths in the first four years of life among children in the 2004 Pelotas (Brazil) birth cohort study. Cad Saude Publica. 2011;27 Suppl 2:S185-97. | Included for systematic reviews not completed
2038 | Santos, I.,Victora, C. G.,Martines, J.,Goncalves, H.,Gigante, D. P.,Valle, N. J.,Pelto, G. Nutrition counseling increases weight gain among Brazilian children. J Nutr. 2001;131(11):2866-73. | Independent variable
2039 | Sarasa Munoz, N. L. Mother’s milk still best--and we must do better. MEDICC Rev. 2013;15(1):48. | Study design
2040 | Sartorius, N. Learning how to speak. Croat Med J. 2007;48(2):259-60. | Study design
2041 | Sasai, K.,Furukawa, S.,Kaneko, K.,Yabuta, K.,Baba, M. Fecal IgE levels in infants at 1 month of age as indicator of atopic disease. Allergy. 1994;49(9):791-4. | Study design
2042 | Sassen, M. L.,Brand, R.,Grote, J. J. Breast-feeding and acute otitis media. Am J Otolaryngol. 1994;15(5):351-7. | Included for systematic reviews not completed
2043 | Sastry, N.,Burgard, S. Changes in Diarrheal Disease and Treatment Among Brazilian Children from 1986 to 1996. Popul Res Policy Rev. 2011;30(1):81-100. | Study design
2044 | Saukkonen, T.,Virtanen, S. M.,Karppinen, M.,Reijonen, H.,Ilonen, J.,Räsänen, L.,. Significance of cow’s milk protein antibodies as risk factor for childhood IDDM: Interactions with dietary cow’s milk intake and HLA-DQB1 genotype. Diabetologia. 1998;41(1):72-78. | Redundant data
2045 | Savilahti, E.,Salmenpera, L.,Tainio, V. M.,Halme, H.,Perheentupa, J.,Siimes, M. A. Prolonged exclusive breast-feeding results in low serum concentrations of immunoglobulin G, A and M. Acta Paediatr Scand. 1987;76(1):1-6. | Independent variable, Dependent variable
2046 | Savilahti, E.,Siltanen, M.,Kajosaari, M.,Vaarala, O.,Saarinen, K. M. IgA antibodies, TGF-beta1 and -beta2, and soluble CD14 in the colostrum and development of atopy by age 4. Pediatr Res. 2005;58(6):1300-5. | Dependent variable
2047 | Savilahti, E.,Tainio, V. M.,Salmenpera, L.,Arjomaa, P.,Kallio, M.,Perheentupa, J.,Siimes, M. A. Levels of IgA and cow milk antibodies in breast milk vs. the development of atopy in children. Low colostral IgA associated with cow milk allergy. Adv Exp Med Biol. 1991;310:417-25. | Independent variable
2048 | Savilahti, E.,Tainio, V. M.,Salmenpera, L.,Siimes, M. A.,Perheentupa, J. Prolonged exclusive breast feeding and heredity as determinants in infantile atopy. Arch Dis Child. 1987;62(3):269-73. | Included for systematic reviews not completed
2049 | Savino, F.,Liguori, S. A.,Benetti, S.,Sorrenti, M.,Fissore, M. F.,Cordero di Montezemolo, L. High serum leptin levels in infancy can potentially predict obesity in childhood, especially in formula-fed infants. Acta Paediatr. 2013;102(10):e455-9. | Included for systematic reviews not completed
2050 | Savino, F.,Maccario, S.,Cresi, F.,Grasso, G.,Oggero, R.,Silvestro, L.,Mussa, G. C. Bioimpedance vector analysis in breastfed and formula-fed infants in the first six months of life. Adv Exp Med Biol. 2004;554:501-4. | Group size
2051 | Savino, F.,Oggero, R.,Prino, A.,Mostert, M.. Hypoantigenic (HA) milk formula and blood cholesterol level in infants at 3 months of age. Acta Paediatr. 1997;86(9):1003-5. | Dependent variable
2052 | Sawchuk, L. A.,Burke, S. D. Mortality in an early Ontario community: Belleville 1876-1885. Urban Hist Rev. 2000;29(1):33-47. | Study design
2053 | Sawley, L. Bottle feeding. Nurs Mirror. 1985;160(3):31-3. | Study design
2054 | Sawley, L. Breast is best. Nurs Mirror. 1985;160(2):15-9. | Study design
2055 | Sawley, L. Infant feeding. Nursing (Lond). 1989;3(39):18-23. | Study design
2056 | Say, G. N.,Karabekiroglu, K.,Babadagi, Z.,Yuce, M. Maternal stress and perinatal features in autism & attention deficit/ hyperactivity disorder. Pediatr Int. 2015. | Included for systematic reviews not completed
2057 | Sayegh, A.,Dini, E. L.,Holt, R. D.,Bedi, R. Caries prevalence and patterns and their relationship to social class, infant feeding and oral hygiene in 4-5-year-old children in Amman, Jordan. Community Dent Health. 2002;19(3):144-51. | Study design
2058 | Sayegh, A.,Dini, E. L.,Holt, R. D.,Bedi, R. Oral health, sociodemographic factors, dietary and oral hygiene practices in Jordanian children. J Dent. 2005;33(5):379-88. | Study design
2059 | Sayyed, T.,Kandil, M.,Bashir, O.,Alnaser, H. The relationship between term pre-eclampsia and the risk of early childhood caries. J Matern Fetal Neonatal Med. 2014;27(1):62-5. | Group size
2060 | Scaglioni, S.,Agostoni, C.,Notaris, R. D.,Radaelli, G.,Radice, N.,Valenti, M.,Giovannini, M.,Riva, E. Early macronutrient intake and overweight at five years of age. Int J Obes Relat Metab Disord. 2000;24(6):777-81. | Included for systematic reviews not completed
2061 | Scalabrin, D.,Mitmesser, S.,Birch, E.,Khoury, J.,Bean, J.,Harris, C.,Berseth, C. Lower incidence and less recurrence of allergic manifestations is observed in children who received docosahexaenoic acid/arachidonic acid in infancy via breast milk or supplemented formula. Allergy: European Journal of Allergy and Clinical Immunology. Conference: 30th Congress of the European Academy of Allergy and Clinical Immunology Istanbul Turkey. Conference Start: 20110611 Conference End: 20110615. Conference Publication: (var.pagings). 2011;66(94):711. | Study design
2062 | Scariati, P. D.,Grummer-Strawn, L. M.,Fein, S. B. A longitudinal analysis of infant morbidity and the extent of breastfeeding in the United States. Pediatrics. 1997;99(6):E5. | Included for systematic reviews not completed
2063 | Scariati, P. D.,Grummer-Strawn, L. M.,Fein, S. B.,Yip, R. Risk of diarrhea related to iron content of infant formula: lack of evidence to support the use of low-iron formula as a supplement for breastfed infants. Pediatrics. 1997;99(3):E2. | Independent variable
2064 | Scarlett D,Cargill M,Lyn-Sue J,Richardson S,McCaw-Binns A. Breastfeeding prevalence among six-week-old infants at University Hospital of the West Indies. West Indian Med J. 1996;45:14-7. | Study design
2065 | Scerri, C.,Savona-Ventura, C. Early metabolic imprinting as a determinant of childhood obesity. International Journal of Diabetes Mellitus. 2010;2(3):175-178. | Study design
2066 | Schach, B.,Haight, M. Colic and food allergy in the breastfed infant: is it possible for an exclusively breastfed infant to suffer from food allergy?. J Hum Lact. 2002;18(1):50-2. | Study design
2067 | Schack-Nielsen, L.,Michaelsen, K. F.,Mortensen, E. L.,Sorensen, T. I.,Reinisch, J. M. Is duration of breastfeeding influencing the risk of obesity in adult males?. Adv Exp Med Biol. 2004;554:383-5. | Study design
2068 | Schack-Nielsen, L.,Molgaard, C.,Larsen, D.,Martyn, C.,Michaelsen, K. F. Arterial compliance in 10-year-old children in relation to breastfeeding. Adv Exp Med Biol. 2004;554:391-3. | Redundant data
2069 | Schack-Nielsen, L.,Sorensen, TIa,Mortensen, E. L.,Michaelsen, K. F. Late introduction of complementary feeding, rather than duration of breastfeeding, may protect against adult overweight. Am J Clin Nutr. 2010;91(3):619-27. | Included for systematic reviews not completed
2070 | Schaefer-Graf, U. M.,Hartmann, R.,Pawliczak, J.,Passow, D.,Abou-Dakn, M.,Vetter, K.,Kordonouri, O. Association of breast-feeding and early childhood overweight in children from mothers with gestational diabetes mellitus. Diabetes Care. 2006;29(5):1105-7. | Study design
2071 | Scheer, B. Caries in children--the dietary factor. Middle East Dent Oral Health. 1985(3):20-2. | Study design
2072 | Scheiwe, A.,Hardy, R.,Watt, R. G. Four-year follow-up of a randomized controlled trial of a social support intervention on infant feeding practices. Matern Child Nutr. 2010;6(4):328-37. | Study design, Independent variable
2073 | Schellscheidt, J.,Ott, A.,Jorch, G. Epidemiological features of sudden infant death after a German intervention campaign in 1992. Eur J Pediatr. 1997;156(8):655-60. | Included for systematic reviews not completed
2074 | Scherdel, P.,Botton, J.,Rolland-Cachera, M. F.,Leger, J.,Pele, F.,Ancel, P. Y.,Simon, C.,Castetbon, K.,Salanave, B.,Thibault, H.,Lioret, S.,Peneau, S.,Gusto, G.,Charles, M. A.,Heude, B. Should the WHO growth charts be used in France?. PLoS One. 2015;10(3):e0120806. | Study design, Independent variable
2075 | Schilithz, A. O.,Kale, P. L.,Gama, S. G.,Nobre, F. F. Risk groups in children under six months of age using self-organizing maps. Comput Methods Programs Biomed. 2014;115(1):1-10. | Study design, Independent variable
2076 | Schluter, P. J.,Durward, C.,Cartwright, S.,Paterson, J. Maternal self-report of oral health in 4-year-old Pacific children from South Auckland, New Zealand: findings from the Pacific Islands Families Study. J Public Health Dent. 2007;67(2):69-77. | Included for systematic reviews not completed
2077 | Schluter, P. J.,Ford, R. P.,Mitchell, E. A.,Taylor, B. J. Residential mobility and sudden infant death syndrome. J Paediatr Child Health. 1998;34(5):432-7. | Independent variable
2078 | Schluter, P. J.,Paterson, J.,Percival, T. Infant care practices associated with sudden infant death syndrome: findings from the Pacific Islands Families study. J Paediatr Child Health. 2007;43(5):388-93. | Study design
2079 | Schmidt BJ. Breast-feeding and infant morbidity and mortality in developing countries. J Pediatr Gastroenterol Nutr. 1983;2 Suppl 1:S127-30. | Study design
2080 | Schmitt, J.,Romanos, M. Prenatal and perinatal risk factors for attention-deficit/hyperactivity disorder. Arch Pediatr Adolesc Med. 2012;166(11):1074-5. | Study design
2081 | Schnitzer, M. E.,Moodie, E. E.,Platt, R. W. Targeted maximum likelihood estimation for marginal time-dependent treatment effects under density misspecification. Biostatistics. 2013;14(1):1-14. | Included for systematic reviews not completed
2082 | Schnitzer, M. E.,van der Laan, M. J.,Moodie, E. E.,Platt, R. W. EFFECT OF BREASTFEEDING ON GASTROINTESTINAL INFECTION IN INFANTS: A TARGETED MAXIMUM LIKELIHOOD APPROACH FOR CLUSTERED LONGITUDINAL DATA. Ann Appl Stat. 2014;8(2):703-725. | Included for systematic reviews not completed
2083 | Schoen, S.,Sichert-Hellert, W.,Kersting, M. Validation of energy requirement equations for estimation of breast milk consumption in infants. Public Health Nutr. 2009;12(12):2309-16. | Dependent variable
2084 | Schoetzau, A.,Filipiak-Pittroff, B.,Franke, K.,Koletzko, S.,Von Berg, A.,Gruebl, A.,Bauer, C. P.,Berdel, D.,Reinhardt, D.,Wichmann, H. E. Effect of exclusive breast-feeding and early solid food avoidance on the incidence of atopic dermatitis in high-risk infants at 1 year of age. Pediatr Allergy Immunol. 2002;13(4):234-42. | Independent variable
2085 | Scholtens, S.,Brunekreef, B.,Smit, H. A.,Gast, G. C.,Hoekstra, M. O.,de Jongste, J. C.,Postma, D. S.,Gerritsen, J.,Seidell, J. C.,Wijga, A. H. Do differences in childhood diet explain the reduced overweight risk in breastfed children?. Obesity (Silver Spring). 2008;16(11):2498-503. | Included for systematic reviews not completed
2086 | Scholtens, S.,Gehring, U.,Brunekreef, B.,Smit, H. A.,de Jongste, J. C.,Kerkhof, M.,Gerritsen, J.,Wijga, A. H. Breastfeeding, weight gain in infancy, and overweight at seven years of age: the prevention and incidence of asthma and mite allergy birth cohort study. Am J Epidemiol. 2007;165(8):919-26. | Included for systematic reviews not completed
2087 | Schroeder, N.,Rushovich, B.,Bartlett, E.,Sharma, S.,Gittelsohn, J.,Caballero, B. Early Obesity Prevention: A Randomized Trial of a Practice-Based Intervention in 0-24-Month Infants. J Obes. 2015;2015:795859. | Independent variable
2088 | Schwartz, R.,Vigo, A.,de Oliveira, L. D.,Justo Giugliani, E. R. The Effect of a Pro-Breastfeeding and Healthy Complementary Feeding Intervention Targeting Adolescent Mothers and Grandmothers on Growth and Prevalence of Overweight of Preschool Children. PLoS One. 2015;10(7):e0131884. | Included for systematic reviews not completed
2089 | Schwartzbaum, J. A.,George, S. L.,Pratt, C. B.,Davis, B. An exploratory study of environmental and medical factors potentially related to childhood cancer. Med Pediatr Oncol. 1991;19(2):115-21. | Study design
2090 | Schwarz, T. Bottle or breast. The first big decision. Nurs Times. 1990;86(35):63-5. | Study design
2091 | Schwarze, C. E.,Hellhammer, D. H.,Stroehle, V.,Lieb, K.,Mobascher, A. Lack of Breastfeeding: A Potential Risk Factor in the Multifactorial Genesis of Borderline Personality Disorder and Impaired Maternal Bonding. J Pers Disord. 2015;29(5):610-26. | Study design, Dependent variable
2092 | Sclavos S,Porter S,Kim Seow W. Future caries development in children with nursing bottle caries. J Pedod. 1988;13:1-10. | Independent variable
2093 | Scott, D. T.,Janowsky, J. S.,Carroll, R. E.,Taylor, J. A.,Auestad, N.,Montalto, M. B. Formula supplementation with long-chain polyunsaturated fatty acids: are there developmental benefits?. Pediatrics. 1998;102(5):E59. | Included for systematic reviews not completed
2094 | Scott, F. W.,Kolb, H. Dietary intervention for diabetes prevention in the neonate. Diabetes Metab Rev. 1998;14(1):106. | Study design
2095 | Scott, J. A.,Ng, S. Y.,Cobiac, L. The relationship between breastfeeding and weight status in a national sample of Australian children and adolescents. BMC Public Health. 2012;12:107. | Study design
2096 | Scott, M.,Roberts, G.,Kurukulaaratchy, R. J.,Matthews, S.,Nove, A.,Arshad, S. H. Multifaceted allergen avoidance during infancy reduces asthma during childhood with the effect persisting until age 18 years. Thorax. 2012;67(12):1046-51. | Independent variable
2097 | Seach, K. A.,Dharmage, S. C.,Lowe, A. J.,Dixon, J. B. Delayed introduction of solid feeding reduces child overweight and obesity at 10 years. Int J Obes (Lond). 2010;34(10):1475-9. | Included for systematic reviews not completed
2098 | Seal, N.,Broome, M. E. Prepregnancy Body Mass Index and Feeding Practices in Relation to Infants’ Growth. J Nurse Pract. 2013;9(5). | Study design
2099 | Sears, M. R.,Greene, J. M.,Willan, A. R.,Taylor, D. R.,Flannery, E. M.,Cowan, J. O.,Herbison, G. P.,Poulton, R. Long-term relation between breastfeeding and development of atopy and asthma in children and young adults: a longitudinal study. Lancet. 2002;360(9337):901-7. | Independent variable
2100 | Seethalakshmi,Rao, K. M. No substitute to mother’s milk. Nurs J India. 1985;76(2):48-9. | Study design
2101 | Seipel, M. M.,Shafer, K. The effect of prenatal and postnatal care on childhood obesity. Soc Work. 2013;58(3):241-52. | Included for systematic reviews not completed
2102 | Selvakumar, B.,Vishnu Bhat, B. Infant feeding practice and its effect on the growth and development of babies. Current Pediatric Research. 2007;11(1-2):13-16. | Country
2103 | Serino, R. J.,Gold, S. B. Infant and early childhood oral health care. N Y State Dent J. 1997;63(2):34-5. | Study design
2104 | Serva, V.,Karim, H.,Ebrahim, G. J. Breast-feeding and the urban poor in developing countries. J Trop Pediatr. 1986;32(3):127-9. | Dependent variable
2105 | Seske, L. M.,Merhar, S. L.,Haberman, B. E. Late-Onset Hypoglycemia in Term Newborns With Poor Breastfeeding. Hosp Pediatr. 2015;5(9):501-4. | Study design
2106 | Sethi, D.,Cumberland, P.,Hudson, M. J.,Rodrigues, L. C.,Wheeler, J. G.,Roberts, J. A.,Tompkins, D. S.,Cowden, J. M.,Roderick, P. J. A study of infectious intestinal disease in England: risk factors associated with group A rotavirus in children. Epidemiol Infect. 2001;126(1):63-70. | Independent variable
2107 | Sethi, V.,Kashyap, S.,Seth, V. Effect of nutrition education of mothers on infant feeding practices. Indian J Pediatr. 2003;70(6):463-6. | Country
2108 | Sezer, R. G.,Aydemir, G.,Akcan, A. B.,Bayoglu, D. S.,Guran, T.,Bozaykut, A. Effect of breastfeeding on serum zinc levels and growth in healthy infants. Breastfeed Med. 2013;8:159-63. | Study design
2109 | Shaaban, K. M.,Hamadnalla, I. The effect of duration of breast feeding on the occurrence of acute otitis media in children under three years. East Afr Med J. 1993;70(10):632-4. | Country
2110 | Shalofsky, Teresa. Telephone peer counselling of breastfeeding among WIC participants: a randomized controlled trial. MIDIRS Midwifery Digest. 2015;25(1):97-98 2p. | Peer review
2111 | Shamir, R.,Nganga, A.,Berkowitz, D.,Diamond, E.,Lischinsky, S.,Lombardo, D.,Shehadeh, N. Serum levels of bile salt-stimulated lipase and breast feeding. J Pediatr Endocrinol Metab. 2003;16(9):1289-94. | Group size
2112 | Shand, N. The reciprocal impact of breast-feeding and culture form on maternal behaviour and infant development. J Biosoc Sci. 1981;13(1):1-17. | Study design, Dependent variable
2113 | Shariff, A. H.,Sazlina, S. G.,Shamsul, A. S. Obesity among urban primary schoolchildren. Journal of Health and Translational Medicine. 2007;10(1):17-20. | Study design
2114 | Sharifzadeh, G. R.,Namakin, K.,Mehrjoofard, H. An epidemiological study on infant mortatity and factors affecting it in rural areas of Birjand, Iran. Iranian Journal of Pediatrics. 2008;18(4):335-342. | Included for systematic reviews not completed
2115 | Sharma, S.,Sood, M.,Sood, A. Environmental risk factors in relation to childhood asthma in rural area. Current Pediatric Research. 2011;15(1):29-32. | Country
2116 | Shaternikov, V. A.,Fateeva, E. M.,Chernikov, M. N. Protein nutrition in early infancy and subsequent periods: its effect on further development. Bibl Nutr Dieta. 1982(31):95-111. | Study design
2117 | Shearrer, G. E.,Whaley, S. E.,Miller, S. J.,House, B. T.,Held, T.,Davis, J. N. Association of gestational diabetes and breastfeeding on obesity prevalence in predominately Hispanic low-income youth. Pediatr Obes. 2015;10(3):165-71. | Study design
2118 | Shehadeh, N.,Weitzer-Kish, H.,Shamir, R.,Shihab, S.,Weiss, R. Impact of early postnatal weight gain and feeding patterns on body mass index in adolescence. J Pediatr Endocrinol Metab. 2008;21(1):9-15. | Included for systematic reviews not completed
2119 | Shelton, K. H.,Collishaw, S.,Rice, F. J.,Harold, G. T.,Thapar, A. Using a genetically informative design to examine the relationship between breastfeeding and childhood conduct problems. Eur Child Adolesc Psychiatry. 2011;20(11-12):571-9. | Study design
2120 | Shepherd, J. Thrush and breastfeeding. Pract Midwife. 2002;5(11):24-7. | Study design
2121 | Shepherd, R. W.,Oxborough, D. B.,Holt, T. L.,Thomas, B. J.,Thong, Y. H. Longitudinal study of the body composition of weight gain in exclusively breast-fed and intake-measured whey-based formula-fed infants to age 3 months. J Pediatr Gastroenterol Nutr. 1988;7(5):732-9. | Included for systematic reviews not completed
2122 | Sherlock, R. L.,Synnes, A. R.,Koehoorn, M. Working mothers and early childhood outcomes: lessons from the Canadian National Longitudinal Study on Children and Youth. Early Hum Dev. 2008;84(4):237-42. | Included for systematic reviews not completed
2123 | Shi, Y.,De Groh, M.,Morrison, H. Perinatal and early childhood factors for overweight and obesity in young Canadian children. Can J Public Health. 2013;104(1):e69-74. | Study design
2124 | Shields, B. M.,Knight, B.,Shakespeare, L.,Babrah, J.,Powell, R. J.,Clark, P. M.,Hattersley, A. T. Determinants of insulin concentrations in healthy 1-week-old babies in the community: applications of a bloodspot assay. Early Hum Dev. 2006;82(2):143-8. | Study design, Dependent variable
2125 | Shields, L.,Mamun, A. A.,O’Callaghan, M.,Williams, G. M.,Najman, J. M. Breastfeeding and obesity at 21 years: a cohort study. J Clin Nurs. 2010;19(11-12):1612-7. | Included for systematic reviews not completed
2126 | Shields, L.,O’Callaghan, M.,Williams, G. M.,Najman, J. M.,Bor, W. Breastfeeding and obesity at 14 years: a cohort study. J Paediatr Child Health. 2006;42(5):289-96. | Included for systematic reviews not completed
2127 | Shohet, L.,Shahar, E.,Davidson, S. Breast feeding as prophylaxis for atopic eczema: a controlled study of 368 cases. Acta Paediatr Hung. 1985;26(1):35-9. | Independent variable
2128 | Shortridge, K. F.,Lawton, J. W.,Choi, E. K. Protective potential of colostrum and early milk against prospective influenza viruses. J Trop Pediatr. 1990;36(2):94-5. | Study design, Dependent variable
2129 | Shu, X. O.,Linet, M. S.,Steinbuch, M.,Wen, W. Q.,Buckley, J. D.,Neglia, J. P.,Potter, J. D.,Reaman, G. H.,Robison, L. L. Breast-feeding and risk of childhood acute leukemia. J Natl Cancer Inst. 1999;91(20):1765-72. | Independent variable
2130 | Sickles, V. S.,Tuley, R. J.,Bader, P.,Carnaggio, V. A.,Exon, W. J.,Hargett, I. R.,Keathley, S. E.,Wolf, R.,Cordano, A. Growth and tolerance studies of a new infant formula. Clin Pediatr (Phila). 1984;23(11):617-22. | Independent variable
2131 | Sidhu, L. S.,Grewal, R.,Bhatnagar, D. P. A study of physical growth in breast-fed and bottle-fed male infants. Indian journal of pediatrics. 1981;48(390):75-79. | Country
2132 | Sievers, E.,Clausen, U.,Oldigs, H. D.,Schaub, J. Supplemental feeding in the first days of life - Effects on the recipient infant. Annals of Nutrition and Metabolism. 2002;46(2):62-67. | Independent variable
2133 | Sievers, E.,Oldigs, H. D.,Dorner, K.,Schaub, J. Longitudinal zinc balances in breast-fed and formula-fed infants. Acta Paediatr. 1992;81(1):1-6. | Group size
2134 | Sievers, E.,Schleyerbach, U.,Garbe-Schonberg, D.,Arpe, T.,Schaub, J. Zinc intakes and plasma concentrations in infancy. Adv Exp Med Biol. 2000;478:383-4. | Study design
2135 | Significance of food hypersensitivity in children with atopic dermatitis. Pediatr Dermatol. 1986;3(2):161-74. | Study design
2136 | Siimes, M. A.,Salmenpera, L.,Perheentupa, J. Exclusive breast-feeding for 9 months: Risk of iron deficiency. Journal of Pediatrics. 1984;104(2):196-199. | Independent variable
2137 | Silberman, S. L.,Trubman, A.,Duncan, W. K.,Meydrech, E. F. Prevalence of primary canine hypoplasia of the mandibular teeth. Pediatr Dent. 1991;13(6):356-60. | Study design
2138 | Siltanen, M.,Kajosaari, M.,Poussa, T.,Saarinen, K. M.,Savilahti, E. A dual long-term effect of breastfeeding on atopy in relation to heredity in children at 4 years of age. Allergy. 2003;58(6):524-30. | Independent variable
2139 | Silva, A. A.,Mehta, Z.,O’Callaghan, F. J. Duration of breast feeding and cognitive function: Population based cohort study. Eur J Epidemiol. 2006;21(6):435-41. | Included for systematic reviews not completed
2140 | Silver, D. H. Improvements in the dental health of 3-year-old Hertfordshire children after 8 years. The relationship to social class. Br Dent J. 1982;153(5):179-83. | Study design
2141 | Simhon, A.,Mata, L. Fecal rotaviruses, adenoviruses, coronavirus-like particles, and small round viruses in a cohort of rural Costa Rican children. Am J Trop Med Hyg. 1985;34(5):931-6. | Independent variable
2142 | Simhon, A.,Mata, L.,Vives, M.,Rivera, L.,Vargas, S.,Ramirez, G.,Lizano, L.,Catarinella, G.,Azofeifa, J. Low endemicity and low pathogenicity of rotaviruses among rural children in Costa Rica. J Infect Dis. 1985;152(6):1134-42. | Study design, Independent variable
2143 | Simon, M. R.,Havstad, S. L.,Wegienka, G. R.,Ownby, D. R.,Johnson, C. C. Risk factors associated with transient wheezing in young children. Allergy Asthma Proc. 2008;29(2):161-5. | Dependent variable
2144 | Sims, D. G.,Gardner, P. S.,Weightman, D.,Turner, M. W.,Soothill, J. F. Atopy does not predispose to RSV bronchiolitis or postbronchiolitic wheezing. Br Med J (Clin Res Ed). 1981;282(6282):2086-8. | Group size
2145 | Singhal, A. Early nutrition and later blood pressure: an experimental approach. Journal of Nutritional & Environmental Medicine. 2002;12(3):251-252 2p. | Study design
2146 | Singhal, A.,Kennedy, K.,Lanigan, J.,Clough, H.,Jenkins, W.,Elias-Jones, A.,Stephenson, T.,Dudek, P.,Lucas, A. Dietary nucleotides and early growth in formula-fed infants: a randomized controlled trial. Pediatrics. 2010;126(4):e946-53. | Included for systematic reviews not completed
2147 | Singhal, A.,Lucas, A. Early origins of cardiovascular disease: is there a unifying hypothesis?. Lancet. 2004;363(9421):1642-5. | Study design
2148 | Singhi, P.,Singhi, S.,Bhalla, A. K. Growth of term infants in early neonatal period. Indian Pediatr. 1985;22(7):485-91. | Country
2149 | Singhi, S.,Singhi, P. Prevention of acute respiratory infections. Indian J Pediatr. 1987;54(2):161-70. | Study design
2150 | Singleton, R.,Lescher, R.,Gessner, B. D.,Benson, M.,Bulkow, L.,Rosenfeld, J.,Thomas, T.,Holman, R. C.,Haberling, D.,Bruce, M.,Bartholomew, M.,Tiesinga, J. Rickets and Vitamin D deficiency in Alaska native children. Journal of Pediatric Endocrinology and Metabolism. 2015;28(7-8):815-823. | Independent variable
2151 | Sinha, A.,Madden, J.,Ross-Degnan, D.,Soumerai, S.,Platt, R. Reduced risk of neonatal respiratory infections among breastfed girls but not boys. Pediatrics. 2003;112(4):e303. | Dependent variable
2152 | Sipila, M.,Karma, P.,Pukander, J.,Timonen, M.,Kataja, M. The Bayesian approach to the evaluation of risk factors in acute and recurrent acute otitis media. Acta Otolaryngol. 1988;106(1-2):94-101. | Included for systematic reviews not completed
2153 | Siriaksorn, S.,Suchaitanawanit, S.,Trakultivakorn, M. Allergic rhinitis and immunoglobulin deficiency in preschool children with frequent upper respiratory illness. Asian Pac J Allergy Immunol. 2011;29(1):73-7. | Study design
2154 | Sjolin, S.,Hofvander, Y.,Hillervik, C. A prospective study of individual courses of breast feeding. Acta paediatrica Scandinavica. 1979;68:521-9. | Dependent variable
2155 | Skilton, M. R.,Marks, G. B.,Ayer, J. G.,Garden, F. L.,Garnett, S. P.,Harmer, J. A.,Leeder, S. R.,Toelle, B. G.,Webb, K.,Baur, L. A.,Celermajer, D. S. Weight gain in infancy and vascular risk factors in later childhood. Pediatrics. 2013;131(6):e1821-8. | Included for systematic reviews not completed
2156 | Skledar, M. T.,Milosevic, M. Breastfeeding and time of complementary food introduction as predictors of obesity in children. Cent Eur J Public Health. 2015;23(1):26-31. | Included for systematic reviews not completed
2157 | Skrodeniene, E.,Marciulionyte, D.,Padaiga, Z.,Jasinskiene, E.,Sadauskaite-Kuehne, V.,Ludvigsson, J. Environmental risk factors in prediction of childhood prediabetes. Medicina (Kaunas). 2008;44(1):56-63. | Dependent variable
2158 | Slabsinskiene E,Milciuviene S,Narbutaite J,Vasiliauskiene I,Andruskeviciene V,Bendoraitiene EA,Saldunaite K. Severe early childhood caries and behavioral risk factors among 3-year-old children in Lithuania. Medicina (Kaunas). 2010;46:135-41. | Study design
2159 | Slae, M.,Persad, R.,Leung, A. J. T.,Gabr, R.,Brocks, D.,Huynh, H. Q. Role of Environmental Factors in the Development of Pediatric Eosinophilic Esophagitis. Digestive Diseases and Sciences. 2015;60(11):3364-3372. | Study design, Dependent variable
2160 | Slavkin, H. C. Streptococcus mutans, early childhood caries and new opportunities. J Am Dent Assoc. 1999;130(12):1787-92. | Study design
2161 | Slykerman, R. F.,Thompson, J. M.,Becroft, D. M.,Robinson, E.,Pryor, J. E.,Clark, P. M.,Wild, C. J.,Mitchell, E. A. Breastfeeding and intelligence of preschool children. Acta Paediatr. 2005;94(7):832-7. | Included for systematic reviews not completed
2162 | Smith, D. P. Breastfeeding in the United States. Soc Biol. 1985;32(1-2):53-60. | Study design, Dependent variable
2163 | Smith, R. M.,Smith, P. A.,McKinnon, M.,Gracey, M. Birthweights and growth of infants in five Aboriginal communities. Aust N Z J Public Health. 2000;24(2):124-35. | Study design
2164 | Smithers, L. G.,Golley, R. K.,Brazionis, L.,Emmett, P.,Northstone, K.,Lynch, J. W. Dietary patterns of infants and toddlers are associated with nutrient intakes. Nutrients. 2012;4(8):935-48. | Dependent variable
2165 | Smithers, L. G.,Golley, R. K.,Mittinty, M. N.,Brazionis, L.,Northstone, K.,Emmett, P.,Lynch, J. W. Dietary patterns at 6, 15 and 24 months of age are associated with IQ at 8 years of age. Eur J Epidemiol. 2012;27(7):525-35. | Independent variable
2166 | Smithers, L. G.,Golley, R. K.,Mittinty, M. N.,Brazionis, L.,Northstone, K.,Emmett, P.,Lynch, J. W. Do dietary trajectories between infancy and toddlerhood influence IQ in childhood and adolescence? Results from a prospective birth cohort study. PLoS One. 2013;8(3):e58904. | Independent variable
2167 | Socha, P.,Grote, V.,Gruszfeld, D.,Janas, R.,Demmelmair, H.,Closa-Monasterolo, R.,Subias, J. E.,Scaglioni, S.,Verduci, E.,Dain, E.,Langhendries, J. P.,Perrin, E.,Koletzko, B. Milk protein intake, the metabolic-endocrine response, and growth in infancy: data from a randomized clinical trial. Am J Clin Nutr. 2011;94(6 Suppl):1776S-1784S. | Dependent variable
2168 | Socha, P.,Janas, R.,Dobrzanska, A.,Koletzko, B.,Broekaert, I.,Brasseur, D.,Sengier, A.,Giovannini, M.,Agostoni, C.,Monasterolo, R. C.,Mendezs, G. Insulin like growth factor regulation of body mass in breastfed and milk formula fed infants. Data from the E.U. Childhood Obesity Programme. Adv Exp Med Biol. 2005;569:159-63. | Study design
2169 | Somech, R.,Tal, G.,Gilad, E.,Mandelberg, A.,Tal, A.,Dalal, I. Epidemiologic, socioeconomic, and clinical factors associated with severity of respiratory syncytial virus infection in previously healthy infants. Clin Pediatr (Phila). 2006;45(7):621-7. | Health status
2170 | Sommerfelt, K.,Ellertsen, B.,Markestad, T. Low birthweight and neuromotor development: a population based, controlled study. Acta Paediatr. 1996;85(5):604-10. | Independent variable, Health status
2171 | Sommerfield, T.,Chalmers, J.,Youngson, G.,Heeley, C.,Fleming, M.,Thomson, G. The changing epidemiology of infantile hypertrophic pyloric stenosis in Scotland. Arch Dis Child. 2008;93(12):1007-11. | Study design, Independent variable, Health status
2172 | Song, N.,Shamssain, M.,Zhang, J.,Wu, J.,Fu, C.,Hao, S.,Guan, J.,Yan, X. Prevalence, severity and risk factors of asthma, rhinitis and eczema in a large group of Chinese schoolchildren. J Asthma. 2014;51(3):232-42. | Study design
2173 | Sonnenschein-van der Voort, A. M.,Jaddoe, V. W.,van der Valk, R. J.,Willemsen, S. P.,Hofman, A.,Moll, H. A.,de Jongste, J. C.,Duijts, L. Duration and exclusiveness of breastfeeding and childhood asthma-related symptoms. Eur Respir J. 2012;39(1):81-9. | Dependent variable
2174 | Soto-Ramirez, N.,Karmaus, W.,Zhang, H.,Davis, S.,Agarwal, S.,Albergottie, A. Modes of infant feeding and the occurrence of coughing/wheezing in the first year of life. J Hum Lact. 2013;29(1):71-80. | Dependent variable
2175 | Soylu, H.,Özgen, Ü,Babalioǧlu, M.,Aras, Ş,Sazak, S. Iron deficiency and iron deficiency anemia in infants and young children at different socioeconomic groups in Istanbul. Turkish Journal of Haematology. 2001;18(1):19-25. | Study design
2176 | Specker, B. L.,Beck, A.,Kalkwarf, H.,Ho, M. Randomized trial of varying mineral intake on total body bone mineral accretion during the first year of life. Pediatrics. 1997;99(6):E12. | Independent variable
2177 | Spyrides, M. H.,Struchiner, C. J.,Barbosa, M. T.,Kac, G. Effect of predominant breastfeeding duration on infant growth: a prospective study using nonlinear mixed effect models. J Pediatr (Rio J). 2008;84(3):237-43. | Language
2178 | Srivastava, S. P.,Sharma, V. K.,Jha, S. P. Mortality patterns in breast versus artificially fed term babies in early infancy: a longitudinal study. Indian Pediatr. 1994;31(11):1393-6. | Country
2179 | Stadler, D. D.,Musser, E. D.,Holton, K. F.,Shannon, J.,Nigg, J. T. Recalled Initiation and Duration of Maternal Breastfeeding Among Children with and Without ADHD in a Well Characterized Case-Control Sample. J Abnorm Child Psychol. 2015. | Study design, Dependent variable
2180 | Stahl, M. D.,Guida, D. A. Slow weight gain in the breast-fed infant: management options. Pediatr Nurs. 1984;10(2):117-20, 164. | Study design
2181 | Stahlberg, M. R. Breast feeding, cow milk feeding, and allergy. Allergy. 1985;40(8):612-5. | Dependent variable
2182 | Stahlberg, M. R.,Ruuskanen, O.,Virolainen, E. Risk factors for recurrent otitis media. Pediatr Infect Dis. 1986;5(1):30-2. | Included for systematic reviews not completed
2183 | Standl, M.,Sausenthaler, S.,Lattka, E.,Koletzko, S.,Bauer, C. P.,Wichmann, H. E.,von Berg, A.,Berdel, D.,Kramer, U.,Schaaf, B.,Lehmann, I.,Herbarth, O.,Klopp, N.,Koletzko, B.,Heinrich, J. FADS gene cluster modulates the effect of breastfeeding on asthma. Results from the GINIplus and LISAplus studies. Allergy. 2012;67(1):83-90. | Independent variable
2184 | Stanfield JP. The influence of malnutrition on development. Practitioner. 1982;226:1929-40. | Study design
2185 | Stanley, E. O.,Lundeen, D. J. Tongue thrust in breast fed and bottle-fed school children: a cross-cultural investigation. Int J Oral Myol. 1980;6(1):6-17. | Independent variable, Dependent variable
2186 | Stanner, S. Is breast best for the heart?. Nutrition Bulletin. 2001;26(3):199-200. | Study design
2187 | Start smart: healthy weight in early childhood. Issue Brief (Grantmakers Health). 2013:1-14. | Study design
2188 | Steady, F. C. Infant feeding in developing countries: combating the multinationals imperative. J Trop Pediatr. 1981;27(4):215-20. | Study design
2189 | Stecksen-Blicks, C.,Granstrom, E.,Silfverdal, S. A.,West, C. E. Prevalence of oral Candida in the first year of life. Mycoses. 2015;58(9):550-6. | Group size
2190 | Steer, C. D.,Davey Smith, G.,Emmett, P. M.,Hibbeln, J. R.,Golding, J. FADS2 polymorphisms modify the effect of breastfeeding on child IQ. PLoS One. 2010;5(7):e11570. | Included for systematic reviews not completed
2191 | Steichen, J. J.,Tsang, R. C. Bone mineralization and growth in term infants fed soy-based or cow milk-based formula. J Pediatr. 1987;110(5):687-92. | Independent variable
2192 | Stein, A. D.,Melgar, P.,Hoddinott, J.,Martorell, R. Cohort profile: The institute of nutrition of central America and Panama (INCAP) nutrition trial cohort study. International Journal of Epidemiology. 2008;37(4):716-720. | Study design
2193 | Stelmach, I.,Bobrowska-Korzeniowska, M.,Smejda, K.,Majak, P.,Jerzynska, J.,Stelmach, W.,Polanska, K.,Sobala, W.,Krysicka, J.,Hanke, W. Risk factors for the development of atopic dermatitis and early wheeze. Allergy Asthma Proc. 2014;35(5):382-9. | Study design
2194 | Stene, L. C.,Joner, G. Atopic disorders and risk of childhood-onset type 1 diabetes in individuals. Clin Exp Allergy. 2004;34(2):201-6. | Study design, Independent variable
2195 | Stenstrom, C.,Ingvarsson, L. Otitis-prone children and controls: a study of possible predisposing factors. 1. Heredity, family background and perinatal period. Acta Otolaryngol. 1997;117(1):87-93. | Included for systematic reviews not completed
2196 | Stepans, M. F. Birthing briefs. Journal of Perinatal Education. 1998;7(1):39-40 2p. | Study design
2197 | Stevens, F. M.,Egan-Mitchell, B.,Cryan, E.,McCarthy, C. F.,McNicholl, B. Decreasing incidence of coeliac disease. Arch Dis Child. 1987;62(5):465-8. | Study design
2198 | Stevens, T. Infant nutrition perspectives. Midwives (1995). 1996;109(1300):120. | Study design
2199 | Stewart, A. J.,Williams, S. M.,Mitchell, E. A.,Taylor, B. J.,Ford, R. P.,Allen, E. M. Antenatal and intrapartum factors associated with sudden infant death syndrome in the New Zealand Cot Death Study. J Paediatr Child Health. 1995;31(5):473-8. | Independent variable
2200 | Stoeckel, J. The intervention research approach to child survival. Asia Pac J Public Health. 1992;6(1):40-5. | Study design
2201 | Stoll, B. J.,Glass, R. I.,Banu, H.,Huq, M. I.,Khan, M. U.,Ahmed, M. Value of stool examination in patients with diarrhoea. Br Med J (Clin Res Ed). 1983;286(6383):2037-40. | Country
2202 | Strabelli, T. M. B.,Botura, C. A.,Maciel, M. A.,Mazzutti, C.,Bridi, A.,Freitas, L. P. Socioeconomic profile of children hospitalized by community acquired pneumonia. Acta Scientiarum - Health Sciences. 2013;35(2):175-179. | Study design, Health status
2203 | Strachan, D. P.,Harkins, L. S.,Johnston, I. D.,Anderson, H. R. Childhood antecedents of allergic sensitization in young British adults. J Allergy Clin Immunol. 1997;99(1 Pt 1):6-12. | Independent variable
2204 | Strachan, D. P.,Taylor, E. M.,Carpenter, R. G. Family structure, neonatal infection, and hay fever in adolescence. Arch Dis Child. 1996;74(5):422-6. | Independent variable
2205 | Strand, T. A.,Sharma, P. R.,Gjessing, H. K.,Ulak, M.,Chandyo, R. K.,Adhikari, R. K.,Sommerfelt, H. Risk factors for extended duration of acute diarrhea in young children. PLoS One. 2012;7(5):e36436. | Country
2206 | Strbak, V.,Hromadova, M.,Kostalova, L.,Kapellerova, A. Search for optimal age for weaning. Ten-year prospective study. Endocr Regul. 1993;27(4):215-21. | Group size
2207 | Strimas, J. H.,Chi, D. S. Significance of IgE level in amniotic fluid and cord blood for the prediction of allergy. Ann Allergy. 1988;61(2):133-6. | Group size
2208 | Strina, A.,Rodrigues, L. C.,Cairncross, S.,Ferrer, S. R.,Fialho, A. M.,Leite, J. P.,Ribeiro, H. C., Jr.,Barreto, M. L. Factors associated with rotavirus diarrhoea in children living in a socially diverse urban centre in Brazil. Trans R Soc Trop Med Hyg. 2012;106(7):445-51. | Study design, Independent variable
2209 | Strobl, W.,Widhalm, K. The natural history of serum lipids and lipoproteins during childhood. Prog Clin Biol Res. 1985;188:101-21. | Study design
2210 | Study hints at link between breastfeeding and intelligence. AHRQ Research Activities. 2006(308):10-10 1p. | Study design
2211 | Study Looks at Breastfeeding Impact on Leukemia. Neonatal Intensive Care. 2015;28(4):12-14 3p. | Study design
2212 | Su, D.,Zhao, Y.,Binns, C.,Scott, J.,Oddy, W. Breast-feeding mothers can exercise: results of a cohort study. Public Health Nutr. 2007;10(10):1089-93. | Independent variable
2213 | Subbarao, P.,Anand, S. S.,Becker, A. B.,Befus, A. D.,Brauer, M.,Brook, J. R.,Denburg, J. A.,Hayglass, K. T.,Kobor, M. S.,Kollmann, T. R.,Kozyrskyj, A. L.,Lou, W. Y. W.,Mandhane, P. J.,Miller, G. E.,Moraes, T. J.,Pare, P. D.,Scott, J. A.,Takaro, T. K.,Turvey, S. E.,Duncan, J. M.,Lefebvre, D. L.,Sears, M. R. The Canadian Healthy Infant Longitudinal Development (CHILD) study: Examining developmental origins of allergy and asthma. Thorax. 2015;70(10):998-1000. | Study design
2214 | Sudden infant death syndrome (SIDS). Canadian Foundation for the Study of Infant Deaths. Canadian Institute of Child Health. Canadian Paediatric Society. Can Fam Physician. 1999;45:702, 709-10. | Study design
2215 | Suganuma, E. K.,Alexander, G. R.,Baruffi, G.,Gilden, S. R. Infant feeding practices in Hawaii. Hawaii Med J. 1988;47(3):112, 117-9. | Study design
2216 | Sun, G.,Jia, G.,Peng, H.,Dickerman, B.,Compher, C.,Liu, J. Trends of childhood obesity in China and associated factors. Clin Nurs Res. 2015;24(2):156-71. | Study design
2217 | Sun, J.,Huo, J.,Zhao, L.,Fu, P.,Wang, J.,Huang, J.,Wang, L.,Song, P.,Fang, Z.,Chang, S.,Yin, S.,Zhang, J.,Ma, G. The nutritional status of young children and feeding practices two years after the Wenchuan Earthquake in the worst-affected areas in China. Asia Pac J Clin Nutr. 2013;22(1):100-8. | Study design, Independent variable
2218 | Sunoto,. Diarrhoeal problems in Southeast Asia. Southeast Asian J Trop Med Public Health. 1982;13(3):306-18. | Study design
2219 | Suoglu, O. D.,Gokce, S.,Saglam, A. T.,Sokucu, S.,Saner, G. Association of Helicobacter pylori infection with gastroduodenal disease, epidemiologic factors and iron-deficiency anemia in Turkish children undergoing endoscopy, and impact on growth. Pediatr Int. 2007;49(6):858-63. | Independent variable
2220 | Surdu, S.,Montoya, L. D.,Tarbell, A.,Carpenter, D. O. Childhood asthma and indoor allergens in Native Americans in New York. Environ Health. 2006;5:22. | Group size
2221 | Sussmann, J. E.,McIntosh, A. M.,Lawrie, S. M.,Johnstone, E. C. Obstetric complications and mild to moderate intellectual disability. Br J Psychiatry. 2009;194(3):224-8. | Independent variable
2222 | Sutmoller, F.,Maia, P. R. Acute respiratory infections in children living in two low income communities of Rio de Janeiro, Brazil. Mem Inst Oswaldo Cruz. 1995;90(6):665-74. | Included for systematic reviews not completed
2223 | Syafruddin, M.,Djauhariah, A. M.,Dasril, D. A study comparing rooming-in with separate nursing. Paediatr Indones. 1988;28(5-6):116-23. | Country
2224 | Tada, A.,Ando, Y.,Hanada, N. Caries risk factors among three-year old children in Chiba, Japan. Asia Pac J Public Health. 1999;11(2):109-12. | Included for systematic reviews not completed
2225 | Tainio, V. M. Lymphocyte subsets in infants: relationships to feeding, atopy, atopic heredity and infections. Int Arch Allergy Appl Immunol. 1985;78(3):305-10. | Dependent variable
2226 | Tainio, V. M.,Savilahti, E.,Salmenpera, L.,Arjomaa, P.,Siimes, M. A.,Perheentupa, J. Risk factors for infantile recurrent otitis media: atopy but not type of feeding. Pediatr Res. 1988;23(5):509-12. | Included for systematic reviews not completed
2227 | Taitz, L. S.,Lukmanji, Z. Alterations in feeding patterns and rates of weight gain in South Yorkshire infants, 1971-1977. Hum Biol. 1981;53(3):313-20. | Study design
2228 | Takala, A. K.,Eskola, J.,Palmgren, J.,Ronnberg, P. R.,Kela, E.,Rekola, P.,Makela, P. H. Risk factors of invasive Haemophilus influenzae type b disease among children in Finland. J Pediatr. 1989;115(5 Pt 1):694-701. | Dependent variable
2229 | Takemura, Y.,Sakurai, Y.,Honjo, S.,Kusakari, A.,Hara, T.,Gibo, M.,Tokimatsu, A.,Kugai, N. Relation between breastfeeding and the prevalence of asthma : the Tokorozawa Childhood Asthma and Pollinosis Study. Am J Epidemiol. 2001;154(2):115-9. | Study design
2230 | Taki, M.,Mizuno, K.,Murase, M.,Nishida, Y.,Itabashi, K.,Mukai, Y. Maturational changes in the feeding behaviour of infants - a comparison between breast-feeding and bottle-feeding. Acta Paediatr. 2010;99(1):61-7. | Group size
2231 | Talayero, J. M. P.,Lizán-García, M.,Puime Á, O.,Muncharaz, M. J. B.,Soto, B. B.,Sánchez-Palomares, M.,Serrano, L. S.,Rivera, L. L. Full breastfeeding and hospitalization as a result of infections in the first year of life. Pediatrics. 2006;118(1):e92-e99. | Included for systematic reviews not completed
2232 | Tanaka, H.,Ishii, H.,Yamada, T.,Akazawa, K.,Nagata, S.,Yamashiro, Y. Growth of Japanese breastfed infants compared to national references and World Health Organization growth standards. Acta Paediatr. 2013;102(7):739-43. | Independent variable
2233 | Tanaka, K.,Miyake, Y.,Sasaki, S. Association between breastfeeding and allergic disorders in Japanese children. Int J Tuberc Lung Dis. 2010;14(4):513-8. | Study design
2234 | Tanaka, K.,Miyake, Y.,Sasaki, S.,Hirota, Y. Infant feeding practices and risk of dental caries in Japan: the Osaka Maternal And Child Health Study. Pediatr Dent. 2013;35(3):267-71. | Included for systematic reviews not completed
2235 | Tanaka, T.,Kato, N. Evaluation of child care practice factors that affect the occurrence of sudden infant death syndrome: Interview conducted by public health nurses. Environmental Health and Preventive Medicine. 2001;6(2):117-120. | Included for systematic reviews not completed
2236 | Taneja, S.,Bhandari, N.,Bahl, R.,Bhan, M. K. Impact of zinc supplementation on mental and psychomotor scores of children aged 12 to 18 months: a randomized, double-blind trial. J Pediatr. 2005;146(4):506-11. | Country
2237 | Tantracheewathorn, S. Growth of breast-fed and formula-fed infants compared with national growth references of Thai children. J Med Assoc Thai. 2005;88(2):168-75. | Included for systematic reviews not completed
2238 | Tantracheewathorn, S.,Lohajaroensub, S. Incidence and risk factors of iron deficiency anemia in term infants. J Med Assoc Thai. 2005;88(1):45-51. | Included for systematic reviews not completed
2239 | Tanzer, F.,Gumuser, C. A study of the growth of 200 newborn babies for a period of 6 months according to the type of nutrition. Ann Trop Paediatr. 1989;9(1):54-8. | Group size
2240 | Targino, A. G.,Rosenblatt, A.,Oliveira, A. F.,Chaves, A. M.,Santos, V. E. The relationship of enamel defects and caries: a cohort study. Oral Dis. 2011;17(4):420-6. | Independent variable
2241 | Tariq, S.,Memon, I. A. Acute otitis media in children. Journal of the College of Physicians and Surgeons Pakistan. 1999;9(12):507-510. | Country
2242 | Tarrant, M.,Fong, D. Y.,Heys, M.,Lee, I. L.,Sham, A.,Hui Choi, E. W. Professional breastfeeding support to increase the exclusivity and duration of breastfeeding: a randomised controlled trial. Hong Kong Med J. 2014;20 Suppl 7:34-5. | Study design, Dependent variable
2243 | Tarrant, M.,Kwok, M. K.,Lam, T. H.,Leung, G. M.,Schooling, C. M. Breast-feeding and childhood hospitalizations for infections. Epidemiology. 2010;21(6):847-54. | Included for systematic reviews not completed
2244 | Tarrant, M.,Schooling, C. M.,Leung, S. L.,Mak, K. H.,Ho, L. M.,Leung, G. M. Impact of breastfeeding on infectious disease hospitalisation: the children of 1997 cohort. Hong Kong Med J. 2014;20 Suppl 4:5-6. | Study design
2245 | Tarrant, R. C.,Sheridan-Pereira, M.,Younger, K. M.,Kearney, J. M. The positive role of breastfeeding on infant health during the first 6 weeks: findings from a prospective observational study based on maternal reports. Ir Med J. 2012;105(3):75-8. | Study design
2246 | Taveras, E. M.,Gillman, M. W.,Kleinman, K. P.,Rich-Edwards, J. W.,Rifas-Shiman, S. L. Reducing racial/ethnic disparities in childhood obesity: the role of early life risk factors. JAMA Pediatr. 2013;167(8):731-8. | Independent variable
2247 | Taveras, E. M.,Gillman, M. W.,Kleinman, K.,Rich-Edwards, J. W.,Rifas-Shiman, S. L. Racial/ethnic differences in early-life risk factors for childhood obesity. Pediatrics. 2010;125(4):686-95. | Included for systematic reviews not completed
2248 | Taveras, E. M.,Rifas-Shiman, S. L.,Scanlon, K. S.,Grummer-Strawn, L. M.,Sherry, B.,Gillman, M. W. To what extent is the protective effect of breastfeeding on future overweight explained by decreased maternal feeding restriction?. Pediatrics. 2006;118(6):2341-8. | Included for systematic reviews not completed
2249 | Tawia S. Childhood obesity and being breastfed. Breastfeed Rev. 2013;21:42-8. | Study design
2250 | Taylor, B. Infant feeding and allergy: fact and fiction. Midwife Health Visit Community Nurse. 1984;20(10):354-60. | Study design
2251 | Taylor, B.,Wadsworth, J. Breast feeding and child development at five years. Dev Med Child Neurol. 1984;26(1):73-80. | Study design
2252 | Taylor, B.,Wadsworth, J.,Golding, J.,Butler, N. Breast feeding, eczema, asthma, and hayfever. J Epidemiol Community Health. 1983;37(2):95-9. | Independent variable
2253 | Taylor, B.,Wadsworth, J.,Golding, J.,Butler, N. Breast-feeding, bronchitis, and admissions for lower-respiratory illness and gastroenteritis during the first five years. Lancet. 1982;1(8283):1227-9. | Independent variable
2254 | Taylor, R. Providing additional guidance and support to parents about sleep, diet and physical activity from birth to 2 years of age: The Prevention of Overweight in Infancy study. Obesity research & clinical practice. 2014;8:102-3. | Peer review
2255 | Taylor-Robinson, D. C.,Williams, H.,Pearce, A.,Law, C.,Hope, S. Do early life exposures explain why more advantaged children get eczema? Findings from the UK Millennium Cohort Study. Br J Dermatol. 2015. | Study design
2256 | Tee, J. H. Some characteristics of 5-year-old children with a dmf of six or more in Gloucestershire, England. Community Dent Health. 1987;4(2):121-8. | Study design
2257 | Teele, D. W.,Klein, J. O.,Rosner, B. Epidemiology of otitis media during the first seven years of life in children in greater Boston: a prospective, cohort study. J Infect Dis. 1989;160(1):83-94. | Included for systematic reviews not completed
2258 | Teixeira Mde, L.,Lira, P. I.,Coutinho, S. B.,Eickmann, S. H.,Lima, M. C. Influence of breastfeeding type and maternal anemia on hemoglobin concentration in 6-month-old infants. J Pediatr (Rio J). 2010;86(1):65-72. | Study design
2259 | Teixeira, Ana Karine Macedo,Menezes, LÃ©a Maria Bezerra de,Dias, Aldo Angelim,Alencar, Carlos Henrique Morais de,Almeida, Maria Eneide LeitÃ£o de. Analysis of protection or risk factors for dental fluorosis in 6 to 8 year-old children in Fortaleza, Brazil. Revista Panamericana de Salud Publica. 2010;28(6):421-428 8p. | Language
2260 | Teka, T.,Faruque, A. S.,Fuchs, G. J. Risk factors for deaths in under-age-five children attending a diarrhoea treatment centre. Acta Paediatr. 1996;85(9):1070-5. | Country
2261 | Telahun, M.,Abdulkadir, J.,Kebede, E. The relation of early nutrition, infections and socio-economic factors to the development of childhood diabetes. Ethiop Med J. 1994;32(4):239-44. | Country
2262 | Temboury, M. C.,Otero, A.,Polanco, I.,Arribas, E. Influence of breast-feeding on the infant’s intellectual development. J Pediatr Gastroenterol Nutr. 1994;18(1):32-6. | Independent variable
2263 | Tenebaum, D.,Gambert, P.,Meunier, S.,d’Athis, P.,Nivelon, J. L.,Lallemand, C. Serum lipoproteins in venous blood serum from birth to the end of the first week: feeding influences. Biol Neonate. 1988;53(3):126-31. | Group size
2264 | Thacher, T. D.,Fischer, P. R.,Tebben, P. J.,Singh, R. J.,Cha, S. S.,Maxson, J. A.,Yawn, B. P. Increasing incidence of nutritional rickets: a population-based study in Olmsted County, Minnesota. Mayo Clin Proc. 2013;88(2):176-83. | Group size
2265 | Thakur, R.,Singh, M. G.,Chaudhary, S.,Manuja, N. Effect of mode of delivery and feeding practices on acquisition of oral Streptococcus mutans in infants. Int J Paediatr Dent. 2012;22(3):197-202. | Country
2266 | Thapa, S.,Short, R. V.,Potts, M. Breast feeding, birth spacing and their effects on child survival. Nature. 1988;335(6192):679-82. | Study design
2267 | Thaver, I. H. “Risk approach” for reducing malnutrition in children from a privileged community. J Pak Med Assoc. 1990;40(3):59-61. | Country
2268 | The Baby-Friendly Hospital Initiative. Birth Gaz. 1998;14:30. | Study design
2269 | Thiering, E.,Bruske, I.,Kratzsch, J.,Thiery, J.,Sausenthaler, S.,Meisinger, C.,Koletzko, S.,Bauer, C. P.,Schaaf, B.,von Berg, A.,Berdel, D.,Lehmann, I.,Herbarth, O.,Kramer, U.,Wichmann, H. E.,Heinrich, J. Prenatal and postnatal tobacco smoke exposure and development of insulin resistance in 10 year old children. Int J Hyg Environ Health. 2011;214(5):361-8. | Independent variable
2270 | Thies, P. A.,Jeris, L. S. Infant feeding practices and dental health. Part 2: breastfeeding and dental caries. Bull Mich Dent Hyg Assoc. 1981;11(1):6-7, 20. | Study design
2271 | Thitasomakul, S.,Piwat, S.,Thearmontree, A.,Chankanka, O.,Pithpornchaiyakul, W.,Madyusoh, S. Risks for early childhood caries analyzed by negative binomial models. J Dent Res. 2009;88(2):137-41. | Group size
2272 | Thomas, G. P.,Soni, N. N. Clinical manifestations and management of nursing bottle syndrome. J Md State Dent Assoc. 1987;30(2):62-4. | Study design
2273 | Thomaz, E. B.,Cangussu, M. C.,Assis, A. M. Maternal breastfeeding, parafunctional oral habits and malocclusion in adolescents: a multivariate analysis. Int J Pediatr Otorhinolaryngol. 2012;76(4):500-6. | Study design
2274 | Thompson, A. L.,Adair, L. S.,Bentley, M. E. Pressuring and restrictive feeding styles influence infant feeding and size among a low-income African-American sample. Obesity (Silver Spring). 2013;21(3):562-71. | Included for systematic reviews not completed
2275 | Thompson, A. L.,Lampl, M. Prenatal and postnatal energetic conditions and sex steroids levels across the first year of life. Am J Hum Biol. 2013;25(5):643-54. | Dependent variable
2276 | Thompson, M. Think zinc. Neonatal Netw. 1987;6(1):44-5. | Study design
2277 | Thompson, N. P.,Montgomery, S. M.,Wadsworth, M. E.,Pounder, R. E.,Wakefield, A. J. Early determinants of inflammatory bowel disease: use of two national longitudinal birth cohorts. Eur J Gastroenterol Hepatol. 2000;12(1):25-30. | Group size
2278 | Thomsen, S. F.,Ulrik, C. S.,Porsbjerg, C.,Backer, V. Early life exposures and risk of atopy among Danish children. Allergy Asthma Proc. 2006;27(2):110-4. | Study design, Dependent variable
2279 | Thomson, J. L.,Tussing-Humphreys, L. M.,Goodman, M. H. Delta Healthy Sprouts: a randomized comparative effectiveness trial to promote maternal weight control and reduce childhood obesity in the Mississippi Delta. Contemp Clin Trials. 2014;38(1):82-91. | Study design, Dependent variable
2280 | Thomson, K.,Morley, R.,Grover, S. R.,Zacharin, M. R. Postnatal evaluation of vitamin D and bone health in women who were vitamin D-deficient in pregnancy, and in their infants. Med J Aust. 2004;181(9):486-8. | Group size
2281 | Thomson, M. Otitis media. How are First Nations children affected?. Can Fam Physician. 1994;40:1943-50. | Study design, Independent variable
2282 | Thorisdottir, A. V.,Ramel, A.,Palsson, G. I.,Tomassson, H.,Thorsdottir, I. Iron status of one-year-olds and association with breast milk, cow’s milk or formula in late infancy. Eur J Nutr. 2013;52(6):1661-8. | Included for systematic reviews not completed
2283 | Thorpe, K.,Rutter, M.,Greenwood, R. Twins as a natural experiment to study the causes of mild language delay: II: Family interaction risk factors. J Child Psychol Psychiatry. 2003;44(3):342-55. | Included for systematic reviews not completed
2284 | Thorsdottir, I.,Gunnarsdottir, I.,Kvaran, M. A.,Gretarsson, S. J. Maternal body mass index, duration of exclusive breastfeeding and children’s development status at the age of 6 years. European Journal of Clinical Nutrition. 2005;59(3):426-431. | Independent variable
2285 | Thorsdottir, I.,Gunnarsdottir, I.,Kvaran, M. A.,Gretarsson, S. J. Maternal body mass index, duration of exclusive breastfeeding and children’s developmental status at the age of 6 years. Eur J Clin Nutr. 2005;59(3):426-31. | Independent variable
2286 | Thorsdottir, I.,Gunnarsdottir, I.,Palsson, G. I.. Birth weight, growth and feeding in infancy: relation to serum lipid concentration in 12-month-old infants. Eur J Clin Nutr. 2003;57(11):1479-85. | Dependent variable
2287 | Thorsdottir, I.,Gunnarsson, B. S. Dietary quality and adequacy of micronutrient intakes in children. Proc Nutr Soc. 2006;65(4):366-75. | Study design
2288 | Thorsdottir, I.,Gunnarsson, B. S.,Atladottir, H.,Michaelsen, K. F.,Palsson, G. Iron status at 12 months of age -- effects of body size, growth and diet in a population with high birth weight. Eur J Clin Nutr. 2003;57(4):505-13. | Included for systematic reviews not completed
2289 | Thurtle, V. Infant feeding. Nurs Mirror. 1985;160(19):44-5. | Study design, Dependent variable
2290 | Timby, N.,Domellof, E.,Hernell, O.,Lonnerdal, B.,Domellof, M. Neurodevelopment, nutrition, and growth until 12 mo of age in infants fed a low-energy, low-protein formula supplemented with bovine milk fat globule membranes: a randomized controlled trial. Am J Clin Nutr. 2014;99(4):860-8. | Independent variable
2291 | Timby, N.,Hernell, O.,Lonnerdal, B.,Domellof, M. Parental feeding control in relation to feeding mode and growth pattern during early infancy. Acta Paediatr. 2014;103(10):1072-7. | Independent variable
2292 | Timby, N.,Hernell, O.,Vaarala, O.,Melin, M.,Lonnerdal, B.,Domellof, M. Infections in infants fed formula supplemented with bovine milk fat globule membranes. J Pediatr Gastroenterol Nutr. 2015;60(3):384-9. | Independent variable
2293 | Timby, N.,Lonnerdal, B.,Hernell, O.,Domellof, M. Cardiovascular risk markers until 12 mo of age in infants fed a formula supplemented with bovine milk fat globule membranes. Pediatr Res. 2014;76(4):394-400. | Independent variable
2294 | Timmermans, F. J.,Gerson, S. Chronic granulomatous otitis media in bottle-fed Inuit children. Can Med Assoc J. 1980;122(5):545-7. | Study design, Independent variable
2295 | Timmermans, M. J.,Dagnelie, P. C.,Theunisz, E. H.,Ewalds, D.,Thijs, C.,Mommers, M.,Arts, I. C. Dietary nucleotide and nucleoside exposure in infancy and atopic dermatitis, recurrent wheeze, and allergic sensitization. J Pediatr Gastroenterol Nutr. 2015;60(5):691-3. | Independent variable
2296 | Tiwari, S. Age of Introduction of Complementary Feeding and Iron Deficiency Anemia in Breastfed Infants,Child Health Viewpoint. Indian Pediatr. 2015;52(11):977-8. | Study design
2297 | Todd, R.,Gelbier, S. Dental caries prevalence in Vietnamese children and teenagers in three London boroughs. Br Dent J. 1990;168(1):24-6. | Study design
2298 | Tom, W. L. Atopic dermatitis: Recent findings and insights. Pediatric Annals. 2012;41(1):1-5. | Study design
2299 | Tomblin, J. B.,Smith, E.,Zhang, X. Epidemiology of specific language impairment: prenatal and perinatal risk factors. J Commun Disord. 1997;30(4):325-43; quiz 343-4. | Included for systematic reviews not completed
2300 | Toms, G. L.,Scott, R. Respiratory syncytial virus and the infant immune response. Arch Dis Child. 1987;62(6):544-6. | Study design, Independent variable
2301 | Toro Monjaraz, E. M.,Ramirez Mayans, J. A.,Cervantes Bustamante, R.,Gomez Morales, E.,Molina Rosales, A.,Montijo Barrios, E.,Zarate Mondragon, F.,Cadena Leon, J.,Cazares Mendez, M.,Lopez-Ugalde, M. Perinatal factors associated with the development of cow’s milk protein allergy. Rev Gastroenterol Mex. 2015;80(1):27-31. | Language, Study design
2302 | Toro, K.,Sotonyi, P. Distribution of prenatal and postnatal risk factors for sudden infant death in Budapest. Scand J Prim Health Care. 2001;19(3):178-80. | Independent variable
2303 | Torowicz, Deborah L.,Spatz, Diane L.,Seelhorst, Amanda. Human Milk and Breastfeeding in the Cardiac Center: A Prospective, Descriptive Study. Journal of Pediatric Healthcare. 2013;27(5):325-325 1p. | Health status
2304 | Torsvik, I. K.,Markestad, T.,Ueland, P. M.,Nilsen, R. M.,Midttun, O.,Bjorke Monsen, A. L. Evaluating iron status and the risk of anemia in young infants using erythrocyte parameters. Pediatr Res. 2013;73(2):214-20. | Group size
2305 | Toschke, A. M.,Beyerlein, A.,von Kries, R. Children at high risk for overweight: a classification and regression trees analysis approach. Obes Res. 2005;13(7):1270-4. | Study design
2306 | Toschke, A. M.,Martin, R. M.,von Kries, R.,Wells, J.,Smith, G. D.,Ness, A. R. Infant feeding method and obesity: body mass index and dual-energy X-ray absorptiometry measurements at 9-10 y of age from the Avon Longitudinal Study of Parents and Children (ALSPAC). Am J Clin Nutr. 2007;85(6):1578-85. | Included for systematic reviews not completed
2307 | Toselli, S.,Zaccagni, L.,Celenza, F.,Albertini, A.,Gualdi-Russo, E. Risk factors of overweight and obesity among preschool children with different ethnic background. Endocrine. 2015;49(3):717-25. | Study design
2308 | Tozzi, A. E.,Bisiacchi, P.,Tarantino, V.,Chiarotti, F.,D’Elia, L.,De Mei, B.,Romano, M.,Gesualdo, F.,Salmaso, S. Effect of duration of breastfeeding on neuropsychological development at 10 to 12 years of age in a cohort of healthy children. Dev Med Child Neurol. 2012;54(9):843-8. | Independent variable
2309 | Trabulsi, J.,Capeding, R.,Lebumfacil, J.,Ramanujam, K.,Feng, P.,McSweeney, S.,Harris, B.,DeRusso, P. Effect of an alpha-lactalbumin-enriched infant formula with lower protein on growth. Eur J Clin Nutr. 2011;65(2):167-74. | Included for systematic reviews not completed
2310 | Tran, T. D.,Biggs, B. A.,Tran, T.,Simpson, J. A.,Hanieh, S.,Dwyer, T.,Fisher, J. Impact on infants’ cognitive development of antenatal exposure to iron deficiency disorder and common mental disorders. PLoS One. 2013;8(9):e74876. | Independent variable, Country
2311 | Trapp, P. G.,Mielke, J. H.,Jorde, L. B.,Eriksson, A. W. Infant mortality patterns in Aland, Finland. Hum Biol. 1983;55(1):131-49. | Study design, Independent variable
2312 | Trevino-Garza, C.,Mancillas-Adame, L.,Villarreal-Perez, J. Z.,De la, O. Cavazos M. E.,Estrada-Zuniga, C. M.,Bosques-Padilla, F. J.,Argente, J. Association between umbilical cord leptin and weight gain according to feeding type in the early postnatal period, a brief report. Rev Invest Clin. 2012;64(6 Pt 2):615-9. | Included for systematic reviews not completed
2313 | Truswell, A. S. ABC of nutrition. Infant feeding. Br Med J (Clin Res Ed). 1985;291(6491):333-7. | Study design
2314 | Tsai, A. I.,Johnsen, D. C.,Lin, Y. H.,Hsu, K. H. A study of risk factors associated with nursing caries in Taiwanese children aged 24-48 months. Int J Paediatr Dent. 2001;11(2):147-9. | Study design
2315 | Tsai, S. F.,Chen, S. J.,Yen, H. J.,Hung, G. Y.,Tsao, P. C.,Jeng, M. J.,Lee, Y. S.,Soong, W. J.,Tang, R. B. Iron deficiency anemia in predominantly breastfed young children. Pediatr Neonatol. 2014;55(6):466-9. | Study design, Health status
2316 | Tsao, P. C.,Chang, F. Y.,Chen, S. J.,Soong, W. J.,Jeng, M. J.,Lee, Y. S.,Yen, H. J.,Yang, C. F.,Tang, R. B. Sudden and unexpected and near death during the early neonatal period: a multicenter study. J Chin Med Assoc. 2012;75(2):65-9. | Study design
2317 | Tse, S. M.,Coull, B. A.,Sordillo, J. E.,Datta, S.,Gold, D. R. Gender- and age-specific risk factors for wheeze from birth through adolescence. Pediatric Pulmonology. 2015;50(10):955-962. | Dependent variable
2318 | Tseng, E.,Potter, S. M.,Picciano, M. F. Dietary protein source and plasma lipid profiles of infants. Pediatrics. 1990;85(4):548-52. | Group size
2319 | Tsubouchi, J.,Higashi, T.,Shimono, T.,Domoto, P. K.,Weinstein, P. A study of baby bottle tooth decay and risk factors for 18-month old infants in rural Japan. ASDC J Dent Child. 1994;61(4):293-8. | Study design
2320 | Tsubouchi, J.,Tsubouchi, M.,Maynard, R. J.,Domoto, P. K.,Weinstein, P. A study of dental caries and risk factors among Native American infants. ASDC J Dent Child. 1995;62(4):283-7. | Study design
2321 | Tu, P. The effects of breastfeeding and birth spacing on child survival in China. Stud Fam Plann. 1989;20(6 Pt 1):332-42. | Study design
2322 | Tulldahl, J.,Pettersson, K.,Andersson, S. W.,Hulthen, L. Mode of infant feeding and achieved growth in adolescence: early feeding patterns in relation to growth and body composition in adolescence. Obes Res. 1999;7(5):431-7. | Independent variable
2323 | Tuncbilek, E.,Uner, S.,Ulusoy, M. Breastfeeding in Turkey: the demographic and socio-economic aspects and relationship with infant/child mortality. Turk J Pediatr. 1983;25(1):3-23. | Study design, Dependent variable
2324 | Turck, D.,Grillon, C.,Lachambre, E.,Robiliard, P.,Beck, L.,Maurin, J. L.,Kempf, C.,Bernet, J. P.,Marx, J.,Lebrun, F.,Van Egroo, L. D. Adequacy and safety of an infant formula with a protein/energy ratio of 1.8 g/100 kcal and enhanced protein efficiency for term infants during the first 4 months of life. J Pediatr Gastroenterol Nutr. 2006;43(3):364-71. | Independent variable
2325 | Turkoglu, S.,Bilgic, A.,Akca, O. F. ADHD symptoms, breast-feeding and obesity in children and adolescents. Pediatr Int. 2015;57(4):546-51. | Study design
2326 | Turner, S.,Zhang, G.,Young, S.,Cox, M.,Goldblatt, J.,Landau, L.,Le Souef, P. Associations between postnatal weight gain, change in postnatal pulmonary function, formula feeding and early asthma. Thorax. 2008;63(3):234-9. | Independent variable
2327 | Tuthill, D. P.,Cosgrove, M.,Dunstan, F.,Stuart, M. L.,Wells, J. C.,Davies, D. P. Randomized double-blind controlled trial on the effects on iron status in the first year between a no added iron and standard infant formula received for three months. Acta Paediatr. 2002;91(2):119-24. | Included for systematic reviews not completed
2328 | Tyler, M.,Hellings, P. Feeding method and rehospitalization in newborns less than 1 month of age. J Obstet Gynecol Neonatal Nurs. 2005;34(1):70-9. | Health status
2329 | Tyson, J.,Burchfield, J.,Sentance, F.,Mize, C.,Uauy, R.,Eastburn, J. Adaptation of feeding to a low fat yield in breast milk. Pediatrics. 1992;89(2):215-20. | Independent variable
2330 | Uauy, R.,Mize, C. E.,Castillo-Duran, C. Fat intake during childhood: metabolic responses and effects on growth. Am J Clin Nutr. 2000;72(5 Suppl):1354S-1360S. | Study design
2331 | Ugur, S.,Haktan, M.,Cakir, E.,Senocak, M.,Telci, A. Serum insulin and blood glucose levels in breast-fed and formula-fed infants in the first week of life. Clin Ther. 1988;10(6):678-87. | Study design
2332 | Uhl, O.,Hellmuth, C.,Demmelmair, H.,Zhou, S. J.,Makrides, M.,Prosser, C.,Lowry, D.,Gibson, R. A.,Koletzko, B. Dietary Effects on Plasma Glycerophospholipids. J Pediatr Gastroenterol Nutr. 2015;61(3):367-72. | Dependent variable
2333 | Uijterschout, L.,Vloemans, J.,Vos, R.,Teunisse, P. P.,Hudig, C.,Bubbers, S.,Verbruggen, S.,Veldhorst, M.,De Leeuw, T.,Van Goudoever, J. B.,Brus, F. Prevalence and risk factors of iron deficiency in healthy young children in the southwestern netherlands. Journal of Pediatric Gastroenterology and Nutrition. 2014;58(2):193-198. | Study design
2334 | Umer, A.,Hamilton, C.,Britton, C. M.,Mullett, M. D.,John, C.,Neal, W.,Lilly, C. L. Association between Breastfeeding and Childhood Obesity: Analysis of a Linked Longitudinal Study of Rural Appalachian Fifth-Grade Children. Child Obes. 2015;11(4):449-55. | Study design
2335 | Unay, B.,Sarici, S. U.,Ulas, U. H.,Akin, R.,Alpay, F.,Gokcay, E. Nutritional effects on auditory brainstem maturation in healthy term infants. Arch Dis Child Fetal Neonatal Ed. 2004;89(2):F177-9. | Group size
2336 | UP11 The Feeding Young Children Study: Preliminary Results from a WIC-based Bottle Weaning Intervention. Journal of Nutrition Education & Behavior. 2012;44(4S1):S83-S83 1p. | Peer review
2337 | Vaarala, O.,Ilonen, J.,Ruohtula, T.,Pesola, J.,Virtanen, S. M.,Harkonen, T.,Koski, M.,Kallioinen, H.,Tossavainen, O.,Poussa, T.,Jarvenpaa, A. L.,Komulainen, J.,Lounamaa, R.,Akerblom, H. K.,Knip, M. Removal of bovine insulin from cow’s milk formula and early initiation of beta-cell autoimmunity in the FINDIA pilot study. Archives of pediatrics & adolescent medicine. 2012;166(7):608-14. | Dependent variable
2338 | Vaarala, O.,Knip, M.,Paronen, J.,Hamalainen, A. M.,Muona, P.,Vaatainen, M.,Ilonen, J.,Simell, O.,Akerblom, H. K. Cow’s milk formula feeding induces primary immunization to insulin in infants at genetic risk for type 1 diabetes. Diabetes. 1999;48(7):1389-94. | Dependent variable
2339 | Vafa, M.,Heshmati, J.,Sadeghi, H.,Shidfar, F.,Namazi, N.,Baradaran, H.,Heydarpour, B.,Jalili, Z.. Is exclusive breastfeeding and its duration related to cardio respiratory fitness in childhood?. J Matern Fetal Neonatal Med. 2015;#volume#(#issue#):1-6. | Study design
2340 | Vaidergorn, B. Oral habits and atypical deglutition in certain Sao Paulo children. Int J Orofacial Myology. 1991;17(3):11-5. | Study design, Independent variable
2341 | Valaitis, R. K.,Ciliska, D. K.,Sheeshka, J. D.,Sword, W. A. Surveying infant feeding practices. Can Nurse. 1996;92(4):21. | Study design
2342 | Valman, H. B. The first year of life: feeding and feeding problems. Br Med J. 1980;280(6212):457-60. | Study design
2343 | Valvi, D.,Mendez, M. A.,Garcia-Esteban, R.,Ballester, F.,Ibarluzea, J.,Goni, F.,Grimalt, J. O.,Llop, S.,Marina, L. S.,Vizcaino, E.,Sunyer, J.,Vrijheid, M. Prenatal exposure to persistent organic pollutants and rapid weight gain and overweight in infancy. Obesity (Silver Spring). 2014;22(2):488-96. | Independent variable
2344 | Van Asperen, P. P.,Kemp, A. S.,Mellis, C. M. Relationship of diet in the development of atopy in infancy. Clin Allergy. 1984;14(6):525-32. | Group size
2345 | Van Biervliet, J. P.,Rosseneu, M.,Caster, H. Influence of dietary factors on the plasma lipoprotein composition and content in neonates. Eur J Pediatr. 1986;144(5):489-93. | Group size
2346 | Van Biervliet, J. P.,Vinaimont, N.,Caster, H.,Vercaemst, R.,Rosseneu, M. Lipoprotein patterns in newborns. Influence of nutritional factors. Acta Cardiol Suppl. 1981;27:69-81. | Group size
2347 | van Biervliet, J. P.,Vinaimont, N.,Caster, H.,Vercaemst, R.,Rosseneu, M. Plasma apoprotein and lipid patterns in newborns: influence of nutritional factors. Acta Paediatr Scand. 1981;70(6):851-6. | Group size
2348 | Van Biervliet, J. P.,Vinaimont, N.,Vercaemst, R.,Rosseneu, M. Serum cholesterol, cholesteryl ester, and high-density lipoprotein development in newborn infants: response to formulas supplemented with cholesterol and gamma-linolenic acid. J Pediatr. 1992;120(4 Pt 2):S101-8. | Group size
2349 | Van Biervliet, S.,Van Biervliet, J. P.,Bernard, D.,Vercaemst, R.,Blaton, V. Serum zinc in healthy Belgian children. Biological Trace Element Research. 2003;94(1):33-40. | Study design
2350 | van Buuren, S. Effects of selective dropout on infant growth standards. Nestle Nutr Workshop Ser Pediatr Program. 2010;65:167-75; discussion 175-9. | Study design
2351 | van den Berg, G.,van Eijsden, M.,Galindo-Garre, F.,Vrijkotte, T. G.,Gemke, R. J. Explaining socioeconomic inequalities in childhood blood pressure and prehypertension: the ABCD study. Hypertension. 2013;61(1):35-41. | Independent variable
2352 | Van Den Berg, G.,Van Eijsden, M.,Galindo-Garre, F.,Vrijkotte, T.,Gemke, R. Low maternal education is associated with increased growth velocity in the first year of life and in early childhood: the ABCD study. Eur J Pediatr. 2013;172(11):1451-7. | Included for systematic reviews not completed
2353 | van den Bogaard, C.,van den Hoogen, H. J.,Huygen, F. J.,van Weel, C. Is the breast best for children with a family history of atopy? The relation between way of feeding and early childhood morbidity. Fam Med. 1993;25(7):471-5. | Independent variable
2354 | van den Bogaard, C.,van den Hoogen, H. J.,Huygen, F. J.,van Weel, C. The relationship between breast-feeding and early childhood morbidity in a general population. Fam Med. 1991;23(7):510-5. | Study design
2355 | Van der Elst, C. W.,Dempster, W. S.,Woods, D. L.,Heese, H. D. Serum zinc and copper in thin mothers, their breast milk and their infants. J Trop Pediatr. 1986;32(3):111-4. | Independent variable, Country
2356 | van der Willik, E. M.,Vrijkotte, T. G.,Altenburg, T. M.,Gademan, M. G.,Kist-van Holthe, J. Exclusively breastfed overweight infants are at the same risk of childhood overweight as formula fed overweight infants. Arch Dis Child. 2015;100(10):932-7. | Independent variable
2357 | van Dijk, C. E.,Innis, S. M. Growth-curve standards and the assessment of early excess weight gain in infancy. Pediatrics. 2009;123(1):102-8. | Independent variable
2358 | van Elten, T. M.,van Rossem, L.,Wijga, A. H.,Brunekreef, B.,de Jongste, J. C.,Koppelman, G. H.,Smit, H. A. Breast milk fatty acid composition has a long-term effect on the risk of asthma, eczema, and sensitization. Allergy. 2015;70(11):1468-76. | Independent variable
2359 | Van Howe, R. S.,Storms, M. R. Blood glucose determinations in large for gestational age infants. Am J Perinatol. 2008;25(5):283-9. | Study design, Independent variable
2360 | van Merode, T.,Maas, T.,Twellaar, M.,Kester, A.,van Schayck, C. P. Gender-specific differences in the prevention of asthma-like symptoms in high-risk infants. Pediatr Allergy Immunol. 2007;18(3):196-200. | Dependent variable
2361 | van Odijk, J.,Hulthen, L.,Ahlstedt, S.,Borres, M. P. Introduction of food during the infant’s first year: a study with emphasis on introduction of gluten and of egg, fish and peanut in allergy-risk families. Acta Paediatr. 2004;93(4):464-70. | Study design, Independent variable
2362 | van Palenstein Helderman, W. H.,Soe, W.,van ‘t Hof, M. A. Risk factors of early childhood caries in a Southeast Asian population. J Dent Res. 2006;85(1):85-8. | Independent variable, Country
2363 | van Rossem, L.,Taveras, E. M.,Gillman, M. W.,Kleinman, K. P.,Rifas-Shiman, S. L.,Raat, H.,Oken, E. Is the association of breastfeeding with child obesity explained by infant weight change?. Int J Pediatr Obes. 2011;6(2-2):e415-22. | Included for systematic reviews not completed
2364 | van Rossem, L.,Wijga, A. H.,Brunekreef, B.,de Jongste, J. C.,Kerkhof, M.,Postma, D. S.,Gehring, U.,Smit, H. A. Overweight in infancy: which pre- and perinatal factors determine overweight persistence or reduction? A birth cohort followed for 11 years. Ann Nutr Metab. 2014;65(2-3):211-9. | Included for systematic reviews not completed
2365 | van Stuijvenberg, M.,Eisses, A. M.,Gruber, C.,Mosca, F.,Arslanoglu, S.,Chirico, G.,Braegger, C. P.,Riedler, J.,Boehm, G.,Sauer, P. J. Do prebiotics reduce the number of fever episodes in healthy children in their first year of life: a randomised controlled trial. Br J Nutr. 2011;106(11):1740-8. | Independent variable
2366 | van Stuijvenberg, M.,Stam, J.,Gruber, C.,Mosca, F.,Arslanoglu, S.,Chirico, G.,Braegger, C. P.,Riedler, J.,Boehm, G.,Sauer, P. J. Similar Occurrence of Febrile Episodes Reported in Non-Atopic Children at Three to Five Years of Age after Prebiotics Supplemented Infant Formula. PLoS One. 2015;10(6):e0129927. | Independent variable
2367 | van t Hof Msc, M. A. The influence of breastfeeding and complementary foods on growth until three years of age in the Euro-Growth Study. Pediatrics. 2000;106(5):1281a-1281. | Independent variable
2368 | van Wouwe, J. P.,van den Hamer, C. J.,van Tricht, J. B. Serum zinc concentrations in exclusively breast-fed infants and in infants fed an adapted formula. Eur J Pediatr. 1986;144(6):598-600. | Study design
2369 | Vandenplas, Y.,Deneyer, M.,Sacre, L.,Loeb, H. Preliminary data on a field study with a new hypo-allergic formula. European Journal of Pediatrics. 1988;148(3):274-277. | Group size
2370 | Vandenplas, Y.,Sacre, L. Influences of neonatal serum IgE concentration, family history and diet on the incidence of cow’s milk allergy. Eur J Pediatr. 1986;145(6):493-5. | Independent variable
2371 | Vanderhoof, J. A.,Murray, N. D.,Antonson, D. L.,Kaufman, S. S. Familial occurrence of protracted diarrhea of infancy. J Pediatr. 1986;109(5):845-7. | Study design
2372 | Vanella, L.,de Gonzalez Lascano, A. M. CD4+, CD8+ cells, IgE and prick test in infants allergic to cow’s milk. Allergol Immunopathol (Madr). 1988;16(5):327-31. | Health status
2373 | Vanessa Nazareth, Isis,Maria Meneses dos Santos, InÃªs,Paula Oliveira GonÃ§alves, Ana,Sena Souza, Ester. RISK FOR CHILD DEVELOPMENT ACCORDING TO THE INTEGRATED ATTENTION STRATEGY TO THE PREVALENT ILLNESSES IN CHILDHOOD. Journal of Nursing UFPE / Revista de Enfermagem UFPE. 2013;7(2):328-336 9p. | Study design, Independent variable
2374 | Varga, G. A comparative study of the social-political determinants of infant and child mortality in Sweden and Hungary 1850-1945. Orvostort Kozl. 2008;54(1-4):5-29. | Study design
2375 | Vasallo, M. I.,Martinez, R.,Ballesta, M. J.,Vives, I.,Sanchez-Solis, M.,Peso, P.,Martinez, C. Effect of an infant formula containing milk fat, Alpha-lactalbumin, Nucleotides and lcpufa on stool patterns in infants. Journal of pediatric gastroenterology and nutrition. 2011;52:E166. | Peer review
2376 | Vazquez, E. 14th annual retrovirus conference (CROI). Astounding choice in breastfeeding: infection or death. Posit Aware. 2007;18(3):29-30. | Study design
2377 | Veereman-Wauters, G.,Staelens, S.,Van de Broek, H.,Plaskie, K.,Wesling, F.,Roger, L. C.,McCartney, A. L.,Assam, P. Physiological and bifidogenic effects of prebiotic supplements in infant formulae. J Pediatr Gastroenterol Nutr. 2011;52(6):763-71. | Group size
2378 | Vehapoglu, A.,Yazici, M.,Demir, A. D.,Turkmen, S.,Nursoy, M.,Ozkaya, E. Early infant feeding practice and childhood obesity: the relation of breast-feeding and timing of solid food introduction with childhood obesity. J Pediatr Endocrinol Metab. 2014;27(11-12):1181-7. | Study design
2379 | Venkataraman, P. S.,Luhar, H.,Neylan, M. J. Bone mineral metabolism in full-term infants fed human milk, cow milk-based, and soy-based formulas. Am J Dis Child. 1992;146(11):1302-5. | Group size
2380 | Vennemann, M. M.,Bajanowski, T.,Brinkmann, B.,Jorch, G.,Yucesan, K.,Sauerland, C.,Mitchell, E. A. Does breastfeeding reduce the risk of sudden infant death syndrome?. Pediatrics. 2009;123(3):e406-10. | Included for systematic reviews not completed
2381 | Vennemann, M. M.,Findeisen, M.,Butterfass-Bahloul, T.,Jorch, G.,Brinkmann, B.,Kopcke, W.,Bajanowski, T.,Mitchell, E. A. Modifiable risk factors for SIDS in Germany: results of GeSID. Acta Paediatr. 2005;94(6):655-60. | Included for systematic reviews not completed
2382 | Vennemann, M.,Bajanowski, T.,Butterfass-Bahloul, T.,Sauerland, C.,Jorch, G.,Brinkmann, B.,Mitchell, E. A. Do risk factors differ between explained sudden unexpected death in infancy and sudden infant death syndrome?. Arch Dis Child. 2007;92(2):133-6. | Included for systematic reviews not completed
2383 | Venter, C.,Pereira, B.,Voigt, K.,Grundy, J.,Clayton, C. B.,Higgins, B.,Arshad, S. H.,Dean, T. Factors associated with maternal dietary intake, feeding and weaning practices, and the development of food hypersensitivity in the infant. Pediatr Allergy Immunol. 2009;20(4):320-7. | Independent variable
2384 | Ventura, A. K.,Loken, E.,Birch, L. L. Developmental trajectories of girls’ BMI across childhood and adolescence. Obesity (Silver Spring). 2009;17(11):2067-74. | Included for systematic reviews not completed
2385 | Ventura, A.,Longo, G.,Longo, F.,Florean, P.,Scornavacca, G. Diet and atopic eczema in children. Allergy. 1989;44 Suppl 9:159-64. | Study design
2386 | Verga, M. E.,Widmeier-Pasche, V.,Beck-Popovic, M.,Pauchard, J. Y.,Gehri, M. Iron deficiency in infancy: is an immigrant more at risk?. Swiss Med Wkly. 2014;144:w14065. | Study design, Independent variable
2387 | Verkasalo, M.,Kuitunen, P.,Savilahti, E.,Tiilikainen, A. Changing pattern of cow’s milk intolerance. An analysis of the occurrence and clinical course in the 60s and mid-70s. Acta Paediatr Scand. 1981;70(3):289-95. | Independent variable, Health status
2388 | Vernacchio, L.,Lesko, S. M.,Vezina, R. M.,Corwin, M. J.,Hunt, C. E.,Hoffman, H. J.,Mitchell, A. A. Racial/ethnic disparities in the diagnosis of otitis media in infancy. Int J Pediatr Otorhinolaryngol. 2004;68(6):795-804. | Study design
2389 | Verstraete, S. G.,Heyman, M. B.,Wojcicki, J. M. Breastfeeding offers protection against obesity in children of recently immigrated Latina women. J Community Health. 2014;39(3):480-6. | Included for systematic reviews not completed
2390 | Vesel, L.,Bahl, R.,Martines, J.,Penny, M.,Bhandari, N.,Kirkwood, B. R. Use of new World Health Organization child growth standards to assess how infant malnutrition relates to breastfeeding and mortality. Bull World Health Organ. 2010;88(1):39-48. | Independent variable
2391 | Vesikari, T.,Prymula, R.,Schuster, V.,Tejedor, J. C.,Cohen, R.,Bouckenooghe, A.,Damaso, S.,Han, H. H. Efficacy and immunogenicity of live-attenuated human rotavirus vaccine in breast-fed and formula-fed European infants. Pediatr Infect Dis J. 2012;31(5):509-13. | Dependent variable
2392 | Vestergaard, M.,Obel, C.,Henriksen, T. B.,Sorensen, H. T.,Skajaa, E.,Ostergaard, J. Duration of breastfeeding and developmental milestones during the latter half of infancy. Acta Paediatr. 1999;88(12):1327-32. | Included for systematic reviews not completed
2393 | Vestman, N. R.,Timby, N.,Holgerson, P. L.,Kressirer, C. A.,Claesson, R.,Domellof, M.,Ohman, C.,Tanner, A. C.,Hernell, O.,Johansson, I. Characterization and in vitro properties of oral lactobacilli in breastfed infants. BMC Microbiol. 2013;13:193. | Study design
2394 | Vichyanond, P. IgE regulation and the control of allergic diseases. Asian Pac J Allergy Immunol. 1990;8(1):1-4. | Study design
2395 | Victora, C. G.,Barros, F. C.,Horta, B. L.,Lima, R. C. Breastfeeding and school achievement in Brazilian adolescents. Acta Paediatr. 2005;94(11):1656-60. | Included for systematic reviews not completed
2396 | Victora, C. G.,Barros, F.,Lima, R. C.,Horta, B. L.,Wells, J. Anthropometry and body composition of 18 year old men according to duration of breast feeding: birth cohort study from Brazil. BMJ. 2003;327(7420):901. | Included for systematic reviews not completed
2397 | Victora, C. G.,Fuchs, S. C.,Flores, J. A.,Fonseca, W.,Kirkwood, B. Risk factors for pneumonia among children in a Brazilian metropolitan area. Pediatrics. 1994;93(6 Pt 1):977-85. | Independent variable
2398 | Victora, C. G.,Hallal, P. C.,Araújo, C. L. P.,Menezes, A. M. B.,Wells, J. C. K.,Barros, F. C. Cohort profile: The 1993 pelotas (Brazil) birth cohort study. International Journal of Epidemiology. 2008;37(4):704-709. | Study design
2399 | Victora, C. G.,Horta, B. L.,Loret de Mola, C.,Quevedo, L.,Pinheiro, R. T.,Gigante, D. P.,Goncalves, H.,Barros, F. C. Association between breastfeeding and intelligence, educational attainment, and income at 30 years of age: a prospective birth cohort study from Brazil. Lancet Glob Health. 2015;3(4):e199-205. | Included for systematic reviews not completed
2400 | Victora, C. G.,Huttly, S. R.,Barros, F. C.,Martines, J. C.,Vaughan, J. P. Prolonged breastfeeding and malnutrition: confounding and effect modification in a Brazilian cohort study. Epidemiology. 1991;2(3):175-81. | Included for systematic reviews not completed
2401 | Victora, C. G.,Huttly, S. R.,Fuchs, S. C.,Nobre, L. C.,Barros, F. C. Deaths due to dysentery, acute and persistent diarrhoea among Brazilian infants. Acta Paediatr Suppl. 1992;381:7-11. | Study design
2402 | Victora, C. G.,Morris, S. S.,Barros, F. C.,de Onis, M.,Yip, R. The NCHS reference and the growth of breast- and bottle-fed infants. J Nutr. 1998;128(7):1134-8. | Independent variable
2403 | Victora, C. G.,Morris, S. S.,Barros, F. C.,Horta, B. L.,Weiderpass, E.,Tomasi, E. Breast-feeding and growth in Brazilian infants. Am J Clin Nutr. 1998;67(3):452-8. | Independent variable
2404 | Victora, C. G.,Rivera, J. A. Optimal child growth and the double burden of malnutrition: Research and programmatic implications. American Journal of Clinical Nutrition. 2014;100(6):1611S-1612S. | Study design
2405 | Victora, C. G.,Smith, P. G.,Barros, F. C.,Vaughan, J. P.,Fuchs, S. C. Risk factors for deaths due to respiratory infections among Brazilian infants. Int J Epidemiol. 1989;18(4):918-25. | Included for systematic reviews not completed
2406 | Victora, C. G.,Smith, P. G.,Vaughan, J. P.,Nobre, L. C.,Lombardi, C.,Teixeira, A. M.,Fuchs, S. C.,Moreira, L. B.,Gigante, L. P.,Barros, F. C. Infant feeding and deaths due to diarrhea. A case-control study. Am J Epidemiol. 1989;129(5):1032-41. | Included for systematic reviews not completed
2407 | Victora, C. G.,Smith, P. G.,Vaughan, J. P.,Nobre, L. C.,Lombardi, C.,Teixeira, A. M.,Fuchs, S. M.,Moreira, L. B.,Gigante, L. P.,Barros, F. C. Evidence for protection by breast-feeding against infant deaths from infectious diseases in Brazil. Lancet. 1987;2(8554):319-22. | Included for systematic reviews not completed
2408 | Victora, C. G.,Vaughan, J. P.,Martines, J. C.,Barcelos, L. B. Is prolonged breast-feeding associated with malnutrition?. Am J Clin Nutr. 1984;39(2):307-14. | Study design
2409 | Viggiano, D.,Fasano, D.,Monaco, G.,Strohmenger, L. Breast feeding, bottle feeding, and non-nutritive sucking; effects on occlusion in deciduous dentition. Arch Dis Child. 2004;89(12):1121-3. | Study design
2410 | Vigi, V.,Chierici, R.,Osti, L.,Fagioli, F.,Rescazzi, R. Serum zinc concentration in exclusively breast-fed infants and in infants fed an adapted formula. Eur J Pediatr. 1984;142(4):245-7. | Group size
2411 | Vignerova, J.,Shriver, L.,Paulova, M.,Brabec, M.,Schneidrova, D.,Ruzkova, R.,Prochazka, B.,Riedlovia, J. Growth of Czech breastfed infants in comparison with the World Health Organization standards. Cent Eur J Public Health. 2015;23(1):32-8. | Independent variable
2412 | Villalpando, S. Feeding mode, infections, and anthropometric status in early childhood. Pediatrics. 2000;106(5):1282-3. | Study design
2413 | Villalpando, S.,Lopez-Alarcon, M. Growth faltering is prevented by breast-feeding in underprivileged infants from Mexico City. J Nutr. 2000;130(3):546-52. | Included for systematic reviews not completed
2414 | Viner, R. M.,Hindmarsh, P. C.,Taylor, B.,Cole, T. J. Childhood body mass index (BMI), breastfeeding and risk of Type 1 diabetes: findings from a longitudinal national birth cohort. Diabet Med. 2008;25(9):1056-61. | Independent variable
2415 | Violato, M.,Petrou, S.,Gray, R.,Redshaw, M. Family income and child cognitive and behavioural development in the United Kingdom: does money matter?. Health Econ. 2011;20(10):1201-25. | Study design, Independent variable
2416 | Virtanen, S. M.,Kenward, M. G.,Erkkola, M.,Kautiainen, S.,Kronberg-Kippila, C.,Hakulinen, T.,Ahonen, S.,Uusitalo, L.,Niinisto, S.,Veijola, R.,Simell, O.,Ilonen, J.,Knip, M. Age at introduction of new foods and advanced beta cell autoimmunity in young children with HLA-conferred susceptibility to type 1 diabetes. Diabetologia. 2006;49(7):1512-21. | Independent variable, Dependent variable
2417 | Virtanen, S. M.,Rasanen, L.,Ylonen, K.,Aro, A.,Clayton, D.,Langholz, B.,Pitkaniemi, J.,Savilahti, E.,Lounamaa, R.,Tuomilehto, J.,et al.,. Early introduction of dairy products associated with increased risk of IDDM in Finnish children. The Childhood in Diabetes in Finland Study Group. Diabetes. 1993;42(12):1786-90. | Redundant data
2418 | Vithayasai, N.,Jennuvat, S. Persistent diarrhea: 15 years experience at a tertiary care hospital. J Med Assoc Thai. 2014;97 Suppl 6:S95-100. | Health status
2419 | Vitolo, M. R.,Bortolini, G. A.,Dal Bo Campagnolo, P.,Feldens, C. A. Effectiveness of a nutrition program in reducing symptoms of respiratory morbidity in children: a randomized field trial. Prev Med. 2008;47(4):384-8. | Dependent variable
2420 | Vitolo, M. R.,Bortolini, G. A.,Feldens, C. A.,Drachler Mde, L. [Impacts of the 10 Steps to Healthy Feeding in Infants: a randomized field trial]. Cadernos de saúde pública. 2005;21(5):1448-57. | Language
2421 | Vivatvakin, B.,Mahayosnond, A.,Theamboonlers, A.,Steenhout, P. G.,Conus, N. J. Effect of a whey-predominant starter formula containing LCPUFAs and oligosaccharides (FOS/GOS) on gastrointestinal comfort in infants. Asia Pac J Clin Nutr. 2010;19(4):473-80. | Dependent variable
2422 | Vobecky, J. S.,Vobecky, J.,Shapcott, D.,Demers, P. P. Nutrient intake patterns and nutritional status with regard to relative weight in early infancy. Am J Clin Nutr. 1983;38(5):730-8. | Included for systematic reviews not completed
2423 | Vogazianos, E.,Vogazianos, P.,Fiala, J.,Janecek, D.,Slapak, I. The effect of breastfeeding and its duration on acute otitis media in children in Brno, Czech Republic. Cent Eur J Public Health. 2007;15(4):143-6. | Study design
2424 | Volz, V. R.,Book, L. S.,Churella, H. R. Growth and plasma amino acid concentrations in term infants fed either whey-predominant formula or human milk. J Pediatr. 1983;102(1):27-31. | Group size
2425 | von Berg, A.,Koletzko, S.,Filipiak-Pittroff, B.,Laubereau, B.,Grubl, A.,Wichmann, H. E.,Bauer, C. P.,Reinhardt, D.,Berdel, D. Certain hydrolyzed formulas reduce the incidence of atopic dermatitis but not that of asthma: three-year results of the German Infant Nutritional Intervention Study. J Allergy Clin Immunol. 2007;119(3):718-25. | Independent variable
2426 | von Berg, A.,Koletzko, S.,Grubl, A.,Filipiak-Pittroff, B.,Wichmann, H. E.,Bauer, C. P.,Reinhardt, D.,Berdel, D. The effect of hydrolyzed cow’s milk formula for allergy prevention in the first year of life: the German Infant Nutritional Intervention Study, a randomized double-blind trial. J Allergy Clin Immunol. 2003;111(3):533-40. | Independent variable
2427 | von Linstow, M. L.,Hogh, M.,Nordbo, S. A.,Eugen-Olsen, J.,Koch, A.,Hogh, B. A community study of clinical traits and risk factors for human metapneumovirus and respiratory syncytial virus infection during the first year of life. Eur J Pediatr. 2008;167(10):1125-33. | Independent variable
2428 | von Mutius, E.,Hartert, T. Update in asthma 2012. Am J Respir Crit Care Med. 2013;188(2):150-6. | Study design
2429 | von Stumm, S.,Plomin, R. Breastfeeding and IQ Growth from Toddlerhood through Adolescence. PLoS One. 2015;10(9):e0138676. | Included for systematic reviews not completed
2430 | Vriezinga, S. L.,Auricchio, R.,Bravi, E.,Castillejo, G.,Chmielewska, A.,Crespo Escobar, P.,Kolacek, S.,Koletzko, S.,Korponay-Szabo, I. R.,Mummert, E.,Polanco, I.,Putter, H.,Ribes-Koninckx, C.,Shamir, R.,Szajewska, H.,Werkstetter, K.,Greco, L.,Gyimesi, J.,Hartman, C.,Hogen Esch, C.,Hopman, E.,Ivarsson, A.,Koltai, T.,Koning, F.,Martinez-Ojinaga, E.,te Marvelde, C.,Pavic, A.,Romanos, J.,Stoopman, E.,Villanacci, V.,Wijmenga, C.,Troncone, R.,Mearin, M. L. Randomized feeding intervention in infants at high risk for celiac disease. N Engl J Med. 2014;371(14):1304-15. | Independent variable
2431 | Wachs, T. D.,Kanashiro, H. C.,Gurkas, P. Intra-individual variability in infancy: structure, stability, and nutritional correlates. Dev Psychobiol. 2008;50(3):217-31. | Independent variable, Dependent variable
2432 | Wadsworth, M. E.,Hardy, R. J.,Paul, A. A.,Marshall, S. F.,Cole, T. J. Leg and trunk length at 43 years in relation to childhood health, diet and family circumstances; evidence from the 1946 national birth cohort. Int J Epidemiol. 2002;31(2):383-90. | Independent variable
2433 | Wagner, V.,von Stockhausen, H. B. The effect of feeding human milk and adapted milk formulae on serum lipid and lipoprotein levels in young infants. Eur J Pediatr. 1988;147(3):292-5. | Study design
2434 | Wahlberg, J.,Vaarala, O.,Ludvigsson, J. Dietary risk factors for the emergence of type 1 diabetes-related autoantibodies in 21/2 year-old Swedish children. Br J Nutr. 2006;95(3):603-8. | Dependent variable
2435 | Walker, W. A. Nucleotides and nutrition: role as dietary supplement. J Nutr. 1994;124(1 Suppl):121s-123s. | Study design, Independent variable, Dependent variable
2436 | Wallis, J. Positive role of breastfeeding during the first six weeks. Midwives. 2012;15(3):31. | Study design
2437 | Walshaw, C. A.,Owens, J. M.,Scally, A. J.,Walshaw, M. J. Does breastfeeding method influence infant weight gain?. Arch Dis Child. 2008;93(4):292-6. | Independent variable
2438 | Walter, T.,Pino, P.,Pizarro, F.,Lozoff, B. Prevention of iron-deficiency anemia: comparison of high- and low-iron formulas in term healthy infants after six months of life. J Pediatr. 1998;132(4):635-40. | Independent variable
2439 | Walton, J. L.,Messer, L. B. Dental caries and fluorosis in breast-fed and bottle-fed children. Caries Res. 1981;15(2):124-37. | Study design
2440 | Wan, A. K.,Seow, W. K.,Purdie, D. M.,Bird, P. S.,Walsh, L. J.,Tudehope, D. I. Oral colonization of Streptococcus mutans in six-month-old predentate infants. J Dent Res. 2001;80(12):2060-5. | Study design
2441 | Wandera, A. Anticipatory guidance in infant oral health. J Mich Dent Assoc. 1998;80(9):28, 55-9. | Study design
2442 | Wang, H.,Wang, A.,Wang, D.,Bright, A.,Sency, V.,Zhou, A.,Xin, B. Early growth and development impairment in patients with ganglioside GM3 synthase deficiency. Clin Genet. 2015. | Dependent variable, Health status
2443 | Wang, I. J.,Guo, Y. L.,Hwang, K. C.,Hsieh, W. S.,Chuang, Y. L.,Lin, S. J.,Chen, P. C. Genetic and environmental predictors for pediatric atopic dermatitis. Acta Paediatrica Taiwanica. 2006;47(5):238-242. | Study design
2444 | Wang, L.,Mamudu, H. M.,Alamian, A.,Anderson, J. L.,Brooks, B. Independent and joint effects of prenatal maternal smoking and maternal exposure to second-hand smoke on the development of adolescent obesity: a longitudinal study. J Paediatr Child Health. 2014;50(11):908-15. | Independent variable
2445 | Wang, X.,Xing, K. H.,Qi, J.,Guan, Y.,Zhang, J. Analysis of the relationship of insulin-like growth factor-1 to the growth velocity and feeding of healthy infants. Growth Horm IGF Res. 2013;23(6):215-9. | Included for systematic reviews not completed
2446 | Wang, Y. S.,Shen, Y. H.,Wang, J. J.,Yang, M. J.,Ding, S. W.,Shi, Y. Y. Preliminary study on the blood glucose level in the exclusively breastfed newborn. J Trop Pediatr. 1994;40(3):187-8. | Independent variable
2447 | Wang, Y. S.,Wu, S. Y. The effect of exclusive breastfeeding on development and incidence of infection in infants. J Hum Lact. 1996;12(1):27-30. | Independent variable
2448 | Wang, Y.,Wang, A.,Donovan, S. M.,Teran-Garcia, M. Individual genetic variations related to satiety and appetite control increase risk of obesity in preschool-age children in the STRONG kids program. Hum Hered. 2013;75(2-4):152-9. | Study design, Independent variable
2449 | Warner, J. O. Food allergy in fully breast-fed infants. Clin Allergy. 1980;10(2):133-6. | Study design
2450 | Warren, J. J.,Bishara, S. E. Duration of nutritive and nonnutritive sucking behaviors and their effects on the dental arches in the primary dentition. Am J Orthod Dentofacial Orthop. 2002;121(4):347-56. | Group size
2451 | Warrington, S.,Storey, D. M. Comparative studies on Asian and Caucasian children. 2: Nutrition, feeding practices and health. Eur J Clin Nutr. 1988;42(1):69-79. | Study design, Independent variable
2452 | Watase, S.,Mourino, A. P.,Tipton, G. A. An analysis of malocclusion in children with otitis media. Pediatr Dent. 1998;20(5):327-30. | Study design
2453 | Watkinson, M. Delayed onset of weanling diarrhoea associated with high breast milk intake. Trans R Soc Trop Med Hyg. 1981;75(3):432-5. | Country
2454 | Watson, E.,Gardner, A.,Carpenter, R. G. An epidemiological and sociological study of unexpected death in infancy in nine areas of southern England. I: Epidemiology. Med Sci Law. 1981;21(2):78-88. | Independent variable
2455 | Watson, P. E.,McDonald, B. W. Subcutaneous body fat in pregnant New Zealand women: association with wheeze in their infants at 18 months. Matern Child Health J. 2013;17(5):959-67. | Study design
2456 | Waylen, A.,Ford, T.,Goodman, R.,Samara, M.,Wolke, D. Can early intake of dietary omega-3 predict childhood externalizing behaviour?. Acta Paediatr. 2009;98(11):1805-8. | Included for systematic reviews not completed
2457 | Weber, F.,Woolridge, M. W.,Baum, J. D. An ultrasonographic study of the organisation of sucking and swallowing by newborn infants. Dev Med Child Neurol. 1986;28(1):19-24. | Dependent variable
2458 | Weber, M.,Grote, V.,Closa-Monasterolo, R.,Escribano, J.,Langhendries, J. P.,Dain, E.,Giovannini, M.,Verduci, E.,Gruszfeld, D.,Socha, P.,Koletzko, B. Lower protein content in infant formula reduces BMI and obesity risk at school age: follow-up of a randomized trial. Am J Clin Nutr. 2014;99(5):1041-51. | Included for systematic reviews not completed
2459 | Weden, M. M.,Brownell, P.,Rendall, M. S. Prenatal, perinatal, early life, and sociodemographic factors underlying racial differences in the likelihood of high body mass index in early childhood. Am J Public Health. 2012;102(11):2057-67. | Included for systematic reviews not completed
2460 | Weerheijm, K. L.,Uyttendaele-Speybrouck, B. F.,Euwe, H. C.,Groen, H. J. Prolonged demand breast-feeding and nursing caries. Caries Res. 1998;32(1):46-50. | Study design
2461 | Weggemann, T.,Brown, J. K.,Fulford, G. E.,Minns, R. A. A study of normal baby movements. Child Care Health Dev. 1987;13(1):41-58. | Group size
2462 | Wegienka, G.,Ownby, D. R.,Havstad, S.,Williams, L. K.,Johnson, C. C. Breastfeeding history and childhood allergic status in a prospective birth cohort. Ann Allergy Asthma Immunol. 2006;97(1):78-83. | Dependent variable
2463 | Wehby, G. L. Breastfeeding and child disability: a comparison of siblings from the United States. Econ Hum Biol. 2014;15:13-22. | Dependent variable
2464 | Weijs, P. J.,Kool, L. M.,van Baar, N. M.,van der Zee, S. C. High beverage sugar as well as high animal protein intake at infancy may increase overweight risk at 8 years: a prospective longitudinal pilot study. Nutr J. 2011;10:95. | Study design
2465 | Weile, B.,Cavell, B.,Nivenius, K.,Krasilnikoff, P. A. Striking differences in the incidence of childhood celiac disease between Denmark and Sweden: a plausible explanation. J Pediatr Gastroenterol Nutr. 1995;21(1):64-8. | Study design, Independent variable, Health status
2466 | Weinstein, P.,Domoto, P.,Wohlers, K.,Koday, M. Mexican-American parents with children at risk for baby bottle tooth decay: pilot study at a migrant farmworkers clinic. ASDC J Dent Child. 1992;59(5):376-83. | Study design
2467 | Weisgerber, M. C.,Lye, P. S.,Nugent, M.,Li, S. H.,De Fouw, K.,Gedeit, R.,Simpson, P.,Gorelick, M. H. Relationship between caloric intake and length of hospital stay for infants with bronchiolitis. Hosp Pediatr. 2013;3(1):24-30. | Health status
2468 | Welch, K. R.,Ariza, A. J.,Wieczorek, J. L.,Binns, H. J. Characteristics of obese children aged 1-4 years at a referral clinic. J Natl Med Assoc. 2008;100(8):884-91. | Study design
2469 | Welford H. Breastfeeding: promoting good practice. Mod Midwife. 1995;5:29-30. | Study design
2470 | Weller, B. F. When is breast best?. Nurs Stand. 1988;3(11):34-5. | Study design
2471 | Welliver, R. C.,Wong, D. T.,Sun, M.,McCarthy, N. Parainfluenza virus bronchiolitis. Epidemiology and pathogenesis. Am J Dis Child. 1986;140(1):34-40. | Included for systematic reviews not completed
2472 | Wells, J. C.,Jonsdottir, O. H.,Hibberd, P. L.,Fewtrell, M. S.,Thorsdottir, I.,Eaton, S.,Lucas, A.,Gunnlaugsson, G.,Kleinman, R. E. Randomized controlled trial of 4 compared with 6 mo of exclusive breastfeeding in Iceland: differences in breast-milk intake by stable-isotope probe. Am J Clin Nutr. 2012;96(1):73-9. | Independent variable
2473 | Wells, J. C.,Stanley, M.,Laidlaw, A. S.,Day, J. M.,Davies, P. S. Energy intake in early infancy and childhood fatness. Int J Obes Relat Metab Disord. 1998;22(5):387-92. | Group size
2474 | Wen, L. M.,Baur, L. A.,Rissel, C.,Simpson, J. M. A randomized controlled trial of an early intervention on childhood obesity: Results from the first 12 months. Obesity (Silver Spring, Md.). 2011;19:S67. | Study design
2475 | Wen, L. M.,Baur, L. A.,Rissel, C.,Xu, H.,Simpson, J. M. Correlates of body mass index and overweight and obesity of children aged 2 years: findings from the healthy beginnings trial. Obesity (Silver Spring). 2014;22(7):1723-30. | Included for systematic reviews not completed
2476 | Wen, L. M.,Baur, L. A.,Simpson, J. M.,Rissel, C.,Wardle, K.,Flood, V. M. Healthy beginnings trial: The journey from the beginning. Obesity research & clinical practice. 2013;7:e2. | Study design
2477 | Wen, X.,Kong, K. L.,Eiden, R. D.,Sharma, N. N.,Xie, C. Sociodemographic differences and infant dietary patterns. Pediatrics. 2014;134(5):e1387-98. | Independent variable
2478 | Wen, X.,Shenassa, E. D.,Paradis, A. D. Maternal smoking, breastfeeding, and risk of childhood overweight: findings from a national cohort. Matern Child Health J. 2013;17(4):746-55. | Included for systematic reviews not completed
2479 | Weng, S. F.,Redsell, S. A.,Nathan, D.,Swift, J. A.,Yang, M.,Glazebrook, C. Estimating overweight risk in childhood from predictors during infancy. Pediatrics. 2013;132(2):e414-21. | Included for systematic reviews not completed
2480 | Werneck, R. I.,Lawrence, H. P.,Kulkarni, G. V.,Locker, D. Early childhood caries and access to dental care among children of Portuguese-speaking immigrants in the city of Toronto. J Can Dent Assoc. 2008;74(9):805. | Study design
2481 | Weston, J. Bottle feeding. Nursing (Lond). 1986;3(2):61-2. | Study design
2482 | Wetzig, H.,Schulz, R.,Diez, U.,Herbarth, O.,Viehweg, B.,Borte, M. Associations between duration of breast-feeding, sensitization to hens’ eggs and eczema infantum in one and two year old children at high risk of atopy. Int J Hyg Environ Health. 2000;203(1):17-21. | Independent variable
2483 | Weyermann, M.,Brenner, H.,Rothenbacher, D. Adipokines in human milk and risk of overweight in early childhood: a prospective cohort study. Epidemiology. 2007;18(6):722-9. | Included for systematic reviews not completed
2484 | Weyermann, M.,Rothenbacher, D.,Brenner, H. Duration of breastfeeding and risk of overweight in childhood: a prospective birth cohort study from Germany. Int J Obes (Lond). 2006;30(8):1281-7. | Included for systematic reviews not completed
2485 | Wheeler, B. J.,Dickson, N. P.,Houghton, L. A.,Ward, L. M.,Taylor, B. J. Incidence and characteristics of vitamin D deficiency rickets in New Zealand children: a New Zealand Paediatric Surveillance Unit study. Aust N Z J Public Health. 2015;39(4):380-3. | Study design, Independent variable
2486 | While A. Infant feeding. Breast versus bottle. Nurs Mirror. 1985;160:30-4. | Study design
2487 | White, C. Breast milk is still a winning formula, says study. Nursing Times. 2000;96(11):12-12 1p. | Study design
2488 | White, V. Breastfeeding and the risk of early childhood caries. Evid Based Dent. 2008;9(3):86-8. | Study design
2489 | Whitehead, R. G. Infant physiology, nutritional requirements, and lactational adequacy. Am J Clin Nutr. 1985;41(2 Suppl):447-58. | Study design, Independent variable
2490 | Whitehead, R. G. Nutritional aspects of human lactation. Lancet. 1983;1(8317):167-9. | Study design
2491 | Whitehead, R. G.,Paul, A. A. Infant growth and human milk requirements. A fresh approach. Lancet. 1981;2(8239):161-3. | Group size
2492 | Whitehead, R. G.,Paul, A. A.,Ahmed, E. A. Weaning practices in the United Kingdom and variations in anthropometric development. Acta Paediatr Scand Suppl. 1986;323:14-23. | Group size
2493 | Whitehouse, A. J.,Robinson, M.,Li, J.,Oddy, W. H. Duration of breast feeding and language ability in middle childhood. Paediatr Perinat Epidemiol. 2011;25(1):44-52. | Included for systematic reviews not completed
2494 | Whitley, E.,Gunnell, D.,Davey Smith, G.,Holly, J. M.,Martin, R. M. Childhood circumstances and anthropometry: the Boyd Orr cohort. Ann Hum Biol. 2008;35(5):518-34. | Study design
2495 | Whitley, E.,Martin, R. M.,Davey Smith, G.,Holly, J. M.,Gunnell, D. The association of childhood height, leg length and other measures of skeletal growth with adult cardiovascular disease: the Boyd-Orr cohort. J Epidemiol Community Health. 2012;66(1):18-23. | Independent variable
2496 | WHO Working Group on the Growth Reference Protocol; WHO Task Force on Methods for the Natural Regulation of Fertility. Growth patterns of breastfed infants in seven countries. Acta Paediatr. 2000;89(2):215-22. | Study design, Independent variable
2497 | Whu, R.,Cirilo, G.,Wong, J.,Finkel, M. L.,Mendez, H. A.,Leggiadro, R. J. Risk factors for pediatric asthma in the South Bronx. J Asthma. 2007;44(10):855-9. | Independent variable
2498 | Wi, C. I.,Park, M. A.,Juhn, Y. J. Development and initial testing of Asthma Predictive Index for a retrospective study: an exploratory study. J Asthma. 2015;52(2):183-90. | Study design
2499 | Wiberger, M.,Eiben, G.,Lissner, L.,Mehlig, K.,Papoutsou, S.,Hunsberger, M. Children consuming milk cereal drink are at increased risk for overweight: The IDEFICS Sweden study, on behalf of the IDEFICS Consortium. Scand J Public Health. 2014;42(6):518-24. | Independent variable
2500 | Wickens, K.,Black, P.,Stanley, T. V.,Mitchell, E.,Barthow, C.,Fitzharris, P. A protective effect of Lactobacillus rhamnosus HN001 against eczema in the first 2 years of life persists to age 4 years. Clinical and Experimental Allergy. 2012;42(7):1071-9. | Independent variable
2501 | Wickman, M.,Melen, E.,Berglind, N.,Lennart Nordvall, S.,Almqvist, C.,Kull, I.,Svartengren, M.,Pershagen, G. Strategies for preventing wheezing and asthma in small children. Allergy. 2003;58(8):742-7. | Independent variable
2502 | Wigg, N. R.,Tong, S.,McMichael, A. J.,Baghurst, P. A.,Vimpani, G.,Roberts, R. Does breastfeeding at six months predict cognitive development?. Aust N Z J Public Health. 1998;22(2):232-6. | Included for systematic reviews not completed
2503 | Wijga, A. H.,Scholtens, S.,Bemelmans, W. J. E.,Kerkhof, M.,Koppelman, G. H.,Brunekreef, B.,Smit, H. A. Diet, screen time, physical activity, and childhood overweight in the general population and in high risk subgroups: prospective analyses in the PIAMA birth cohort. Journal of Obesity. 2010:9p-9p 1p. | Included for systematic reviews not completed
2504 | Willatts, P.,Forsyth, S.,Agostoni, C.,Casaer, P.,Riva, E.,Boehm, G. Effects of long-chain PUFA supplementation in infant formula on cognitive function in later childhood. Am J Clin Nutr. 2013;98(2):536S-42S. | Independent variable
2505 | Williams, D. M.,Martin, R. M.,Davey Smith, G.,Alberti, K. G.,Ben-Shlomo, Y.,McCarthy, A. Associations of infant nutrition with insulin resistance measures in early adulthood: evidence from the Barry-Caerphilly Growth (BCG) study. PLoS One. 2012;7(3):e34161. | Independent variable
2506 | Williams, S. A.,Hargreaves, J. A. An inquiry into the effects of health related behaviour on dental health among young Asian children resident in a fluoridated city in Canada. Community Dent Health. 1990;7(4):413-20. | Study design
2507 | Williams, S. M.,Taylor, B. J.,Ford, R. P.,Nelson, E. A. Growth velocity before sudden infant death. Arch Dis Child. 1990;65(12):1315-8. | Independent variable
2508 | Williams, S. M.,Taylor, B. J.,Mitchell, E. A.,Scragg, R.,Ford, R. P.,Stewart, A. W. Sudden infant death syndrome in New Zealand: are risk scores useful? New Zealand National Cot Death Study Group. J Epidemiol Community Health. 1995;49(1):94-101. | Included for systematic reviews not completed
2509 | Williams, S. M.,Taylor, R. W.,Taylor, B. J. Secular changes in BMI and the associations between risk factors and BMI in children born 29 years apart. Pediatr Obes. 2013;8(1):21-30. | Included for systematic reviews not completed
2510 | Williamson, E.,Morley, R.,Lucas, A.,Carpenter, J. Propensity scores: from naive enthusiasm to intuitive understanding. Stat Methods Med Res. 2012;21(3):273-93. | Study design, Health status
2511 | Williamson, I. G.,Dunleavey, J.,Robinson, D. Risk factors in otitis media with effusion. A 1 year case control study in 5-7 year old children. Fam Pract. 1994;11(3):271-4. | Independent variable
2512 | Willows, N. D.,Dewailly, E.,Gray-Donald, K. Anemia and iron status in Inuit infants from northern Quebec. Can J Public Health. 2000;91(6):407-10. | Included for systematic reviews not completed
2513 | Wilson, C. E. Cree infant care practices and sudden infant death syndrome. Can J Public Health. 2000;91(2):133-6. | Study design, Dependent variable
2514 | Wingard, D. L.,Criqui, M. H.,Edelstein, S. L.,Tucker, J.,Tomlinson-Keasey, C.,Schwartz, J. E.,Friedman, H. S. Is breast-feeding in infancy associated with adult longevity?. Am J Public Health. 1994;84(9):1458-62. | Dependent variable
2515 | Wojcicki, J. M.,Young, M. B.,Perham-Hester, K. A.,de Schweinitz, P.,Gessner, B. D. Risk factors for obesity at age 3 in Alaskan children, including the role of beverage consumption: results from Alaska PRAMS 2005-2006 and its three-year follow-up survey, CUBS, 2008-2009. PLoS One. 2015;10(3):e0118711. | Included for systematic reviews not completed
2516 | Wolman, P. G. Feeding practices in infancy and prevalence of obesity in preschool children. J Am Diet Assoc. 1984;84(4):436-8. | Included for systematic reviews not completed
2517 | Wong, H. B. Child health in Singapore--past, present and future. Ann Acad Med Singapore. 1982;11(3):322-35. | Study design
2518 | Wong, W. W.,Hachey, D. L.,Insull, W.,Opekun, A. R.,Klein, P. D. Effect of dietary cholesterol on cholesterol synthesis in breast-fed and formula-fed infants. J Lipid Res. 1993;34(8):1403-11. | Group size
2519 | Woo, J. G.,Guerrero, M. L.,Ruiz-Palacios, G. M.,Peng, Y. M.,Herbers, P. M.,Yao, W.,Ortega, H.,Davidson, B. S.,McMahon, R. J.,Morrow, A. L. Specific infant feeding practices do not consistently explain variation in anthropometry at age 1 year in urban United States, Mexico, and China cohorts. J Nutr. 2013;143(2):166-74. | Included for systematic reviews not completed
2520 | Wood, C. S.,Isaacs, P. C.,Jensen, M.,Hilton, H. G. Exclusively breast-fed infants: growth and caloric intake. Pediatr Nurs. 1988;14(2):117-24. | Group size
2521 | Wood, R.,Stockton, D.,Brown, H. Moving from a universal to targeted child health programme: which children receive enhanced care? A population-based study using routinely available data. Child Care Health Dev. 2013;39(6):772-81. | Dependent variable
2522 | Woodward, A.,Douglas, R. M.,Graham, N. M.,Miles, H. Acute respiratory illness in Adelaide children: breast feeding modifies the effect of passive smoking. J Epidemiol Community Health. 1990;44(3):224-30. | Included for systematic reviews not completed
2523 | Worobey, J. Effects of feeding method on infant temperament. Adv Child Dev Behav. 1993;24:37-61. | Study design
2524 | Wray, J. Breastfeeding and primitive neonatal reflexes. Pract Midwife. 2008;11(5):53-6. | Study design
2525 | Wright Mda, G.,Dutra de Oliveira, J. E. Is breast feeding the solution to the infant nutrition problem in underdeveloped countries?. Child Care Health Dev. 1986;12(6):359-68. | Study design
2526 | Wright, A. L.,Bauer, M.,Naylor, A.,Sutcliffe, E.,Clark, L. Increasing breastfeeding rates to reduce infant illness at the community level. Pediatrics. 1998;101(5):837-44. | Included for systematic reviews not completed
2527 | Wright, A. L.,Holberg, C. J.,Martinez, F. D.,Morgan, W. J.,Taussig, L. M. Breast feeding and lower respiratory tract illness in the first year of life. Group Health Medical Associates. BMJ. 1989;299(6705):946-9. | Included for systematic reviews not completed
2528 | Wright, A. L.,Holberg, C. J.,Taussig, L. M.,Martinez, F. D. Factors influencing the relation of infant feeding to asthma and recurrent wheeze in childhood. Thorax. 2001;56(3):192-7. | Redundant data
2529 | Wright, A. L.,Holberg, C. J.,Taussig, L. M.,Martinez, F. D.. Relationship of infant feeding to recurrent wheezing at age 6 years. Arch Pediatr Adolesc Med. 1995;149(7):758-63. | Included for systematic reviews not completed
2530 | Wright, A. L.,Holberg, C. J.,Taussig, L. M.,Martinez, F. Maternal asthma status alters relation of infant feeding to asthma in childhood. Adv Exp Med Biol. 2000;478:131-7. | Independent variable
2531 | Wright, A. L.,Stern, D. A.,Halonen, M. The association of allergic sensitization in mother and child in breast-fed and formula-fed infants. Adv Exp Med Biol. 2001;501:249-55. | Dependent variable
2532 | Wright, C. J.,Atkinson, F. S.,Ramalingam, N.,Buyken, A. E.,Brand-Miller, J. C. Effects of human milk and formula on postprandial glycaemia and insulinaemia. Eur J Clin Nutr. 2015;69(8):939-43. | Age
2533 | Wright, C. M.,Parkinson, K.,Scott, J. Breast-feeding in a UK urban context: who breast-feeds, for how long and does it matter?. Public Health Nutr. 2006;9(6):686-91. | Included for systematic reviews not completed
2534 | Wright, C. M.,Stone, D. H.,Parkinson, K. N. Undernutrition in British Haredi infants within the Gateshead Millennium cohort study. Arch Dis Child. 2010;95(8):630-3. | Included for systematic reviews not completed
2535 | Wright, C.,Lakshman, R.,Emmett, P.,Ong, K. K. Implications of adopting the WHO 2006 Child Growth Standard in the UK: two prospective cohort studies. Arch Dis Child. 2008;93(7):566-9. | Independent variable
2536 | Wright, P. Development of feeding behaviour in early infancy: implications for obesity. Health Bull (Edinb). 1981;39(3):197-205. | Study design, Independent variable
2537 | Wu, T. C.,Huang, I. F.,Chen, Y. C.,Chen, P. H.,Yang, L. Y.. Differences in serum biochemistry between breast-fed and formula-fed infants. J Chin Med Assoc. 2011;74(11):511-5. | Included for systematic reviews not completed
2538 | Wu, T. C.,Hwang, B. Blood nutrient indices in breast and formula fed infants: amino acids metabolic responses. Zhonghua Min Guo Xiao Er Ke Yi Xue Hui Za Zhi. 1997;38(5):345-51. | Included for systematic reviews not completed
2539 | Wyne, A. H.,Adenubi, J. O.,Shalan, T.,Khan, N. Feeding and socioeconomic characteristics of nursing caries children in a Saudi population. Pediatr Dent. 1995;17(7):451-4. | Study design
2540 | Xenellis, J.,Paschalidis, J.,Georgalas, C.,Davilis, D.,Tzagaroulakis, A.,Ferekidis, E. Factors influencing the presence of otitis media with effusion 16 months after initial diagnosis in a cohort of school-age children in rural Greece: a prospective study. Int J Pediatr Otorhinolaryngol. 2005;69(12):1641-7. | Health status
2541 | Xie, L. L.,Jiang, L. Arterial ischemic stroke and hemorrhagic stroke in Chinese children: a retrospective analysis. Brain Dev. 2014;36(2):153-8. | Dependent variable, Health status
2542 | Yadav, M.,Akobeng, A. K.,Thomas, A. G. Breast-feeding and childhood obesity. J Pediatr Gastroenterol Nutr. 2000;30(3):345-6. | Study design
2543 | Yakubov, R.,Nadir, E.,Stein, R.,Klein-Kremer, A. The Duration of Breastfeeding and Its Association with Metabolic Syndrome among Obese Children. ScientificWorldJournal. 2015;2015:731319. | Study design
2544 | Yalcin, S. S.,Hizli, S.,Yurdakok, K.,Ozmert, E. Risk factors for hospitalization in children with acute diarrhea: a case control study. Turk J Pediatr. 2005;47(4):339-42. | Health status
2545 | Yalcin, S. S.,Turul, B.,Cetinkaya, S.,Cakir, B.,Yilmaz, A. Effect of total attending period on infection episode rate in a child-care center. Pediatr Int. 2004;46(5):555-60. | Included for systematic reviews not completed
2546 | Yamakawa, M.,Yorifuji, T.,Inoue, S.,Kato, T.,Doi, H. Breastfeeding and obesity among schoolchildren: a nationwide longitudinal survey in Japan. JAMA Pediatr. 2013;167(10):919-25. | Included for systematic reviews not completed
2547 | Yamakawa, M.,Yorifuji, T.,Kato, T.,Inoue, S.,Tokinobu, A.,Tsuda, T.,Doi, H. Long-Term Effects of Breastfeeding on Children’s Hospitalization for Respiratory Tract Infections and Diarrhea in Early Childhood in Japan. Matern Child Health J. 2015;19(9):1956-65. | Included for systematic reviews not completed
2548 | Yamakawa, M.,Yorifuji, T.,Kato, T.,Yamauchi, Y.,Doi, H. Breast-feeding and hospitalization for asthma in early childhood: a nationwide longitudinal survey in Japan. Public Health Nutr. 2015;18(10):1756-61. | Independent variable
2549 | Yamauchi, Y.,Yamanouchi, I. The relationship between rooming-in/not rooming-in and breast-feeding variables. Acta Paediatr Scand. 1990;79(11):1017-22. | Independent variable
2550 | Yamauchi, Y.,Yamanouchi, I. The relationship between rooming-in/not rooming-in and breastfeeding variables. Breastfeeding Review. 1992;2(5):238-241 4p. | Independent variable
2551 | Yamborisut, U.,Kosulwat, V.,Chittchang, U.,Wimonpeerapattana, W.,Suthutvoravut, U. Factors associated with dual form of malnutrition in school children in Nakhon Pathom and Bangkok. J Med Assoc Thai. 2006;89(7):1012-23. | Study design
2552 | Yang, S.,Fombonne, E.,Kramer, M. S. Duration of gestation, size at birth and later childhood behaviour. Paediatr Perinat Epidemiol. 2011;25(4):377-87. | Independent variable
2553 | Yang, S.,Platt, R. W.,Dahhou, M.,Kramer, M. S. Do population-based interventions widen or narrow socioeconomic inequalities? The case of breastfeeding promotion. Int J Epidemiol. 2014;43(4):1284-92. | Included for systematic reviews not completed
2554 | Ye, M.,Mandhane, P. J.,Senthilselvan, A. Association of breastfeeding with asthma in young Aboriginal children in Canada. Can Respir J. 2012;19(6):361-6. | Study design
2555 | Ye, W.,Feng, X. P.,Liu, Y. L. Epidemiological study of the risk factors of rampant caries in Shanghai children. Chin J Dent Res. 1999;2(2):58-62. | Study design
2556 | Yeung, D. L.,Pennell, M. D.,Leung, M.,Hall, J. Infant fatness and feeding practices: a longitudinal assessment. J Am Diet Assoc. 1981;79(5):531-5. | Included for systematic reviews not completed
2557 | Yeung, K. A.,Taylor, T.,Scheimann, A.,Carvalho, R.,Reinhardt, E.,Girolami, P.,Wood, R. The Prevalence of Food Allergies in Children Referred to a Multidisciplinary Feeding Program. Clin Pediatr (Phila). 2015;54(11):1081-6. | Health status
2558 | Yi, M. J.,Sun, D. F.,Zhou, X. B. Relationship between infant breast feeding and simple obesity in preschool children: A case-control study. Chinese Journal of Clinical Rehabilitation. 2003;7(30):4088-4089. | Study design
2559 | Yi, M. J.,Sun, M. H.,Liu, F.,Liu, Y. Association between infant breastfeeding and temperamental characteristics development in children aged 4-5 years. Journal of Clinical Rehabilitative Tissue Engineering Research. 2007;11(30):6100-6102. | Study design
2560 | Yildirim, Ş,Binnetoğlu, F. K.,Aylanç, H.,Battal, F.,Tekin, M.,Kaymaz, N.,Topaloğlu, N.,A§Ik, Z. Effect of infant feeding on epicardial fat thickness in normal weighted children. Anatolian Journal of Clinical Investigation. 2015;9(3):92-97. | Study design, Health status
2561 | Yimyaem, P.,Chongsrisawat, V.,Vivatvakin, B.,Wisedopas, N. Gastrointestinal manifestations of cow’s milk protein allergy during the first year of life. J Med Assoc Thai. 2003;86(2):116-23. | Study design
2562 | Yin, J.,Quinn, S.,Dwyer, T.,Ponsonby, A. L.,Jones, G. Maternal diet, breastfeeding and adolescent body composition: a 16-year prospective study. Eur J Clin Nutr. 2012;66(12):1329-34. | Included for systematic reviews not completed
2563 | Yip R,Parvanta I,Scanlon K,Borland EW,Russell CM,Trowbridge FL. Pediatric nutrition surveillance system--United States, 1980-1991. MMWR CDC Surveill Summ. 1992;41:1-24. | Independent variable, Dependent variable
2564 | Yiş, U.,Öztürk, Y.,Şişman, A. R.,Uysal, S.,Soylu Ö, B.,Büyükgebiz, B. The relation of serum ghrelin, leptin and insulin levels to the growth patterns and feeding characteristics in breast-fed versus formula-fed infants. Turkish Journal of Pediatrics. 2010;52(1):35-41. | Group size
2565 | Yoneyama, K.,Nagata, H.,Asano, H. Growth of Japanese breast-fed and bottle-fed infants from birth to 20 months. Ann Hum Biol. 1994;21(6):597-608. | Independent variable
2566 | Yonezu, T.,Ushida, N.,Yakushiji, M. Longitudinal study of prolonged breast- or bottle-feeding on dental caries in Japanese children. Bull Tokyo Dent Coll. 2006;47(4):157-60. | Included for systematic reviews not completed
2567 | Yonezu, T.,Yotsuya, K.,Yakushiji, M. Characteristics of breast-fed children with nursing caries. Bull Tokyo Dent Coll. 2006;47(4):161-5. | Study design, Independent variable
2568 | Yoon, H. S.,Shin, Y. J.,Ki, M. Risk factors for neonatal infections in full-term babies in South Korea. Yonsei Medical Journal. 2008;49(4):530-536. | Dependent variable
2569 | Yorifuji, T.,Kubo, T.,Yamakawa, M.,Kato, T.,Inoue, S.,Tokinobu, A.,Doi, H. Breastfeeding and behavioral development: a nationwide longitudinal survey in Japan. J Pediatr. 2014;164(5):1019-1025 e3. | Included for systematic reviews not completed
2570 | Young, H. B.,Buckley, A. E.,Hamza, B.,Mandarano, C. Milk and lactation: some social and developmental correlates among 1,000 infants. Pediatrics. 1982;69(2):169-75. | Independent variable
2571 | Young, R. J.,Antonson, D. L.,Ferguson, P. W.,Murray, N. D.,Merkel, K.,Moore, T. E. Neonatal and infant feeding: effect on bone density at 4 years. J Pediatr Gastroenterol Nutr. 2005;41(1):88-93. | Included for systematic reviews not completed
2572 | Young, S.,O’Keeffe, P. T.,Arnott, J.,Landau, L. I. Lung function, airway responsiveness, and respiratory symptoms before and after bronchiolitis. Arch Dis Child. 1995;72(1):16-24. | Study design, Independent variable, Group size
2573 | Yu, C.,Binns, C. W.,Lee, A. H. Comparison of breastfeeding rates and health outcomes for infants receiving care from hospital outpatient clinic and community health centres in China. J Child Health Care. 2015. | Included for systematic reviews not completed
2574 | Yu, L. X.,Tao, Y.,Qiu, R. M.,Zhou, Y.,Zhi, Q. H.,Lin, H. C. Genetic polymorphisms of the sortase A gene and social-behavioural factors associated with caries in children: a case-control study. BMC Oral Health. 2015;15:54. | Study design
2575 | Yuksel, H.,Sakar, A.,Dinc, G.,Yilmaz, O.,Gozmen, S.,Yorgancioglu, A.,Ozcan, C. The frequency of wheezing phenotypes and risk factors for persistence in aegean region of Turkey. J Asthma. 2007;44(2):89-93. | Study design
2576 | Yung, J.,Yuen, J. W. M.,Ou, Y.,Loke, A. Y. Factors associated with atopy in toddlers: A case-control study. International Journal of Environmental Research and Public Health. 2015;12(3):2501-2520. | Study design
2577 | Yurdakok, K.,Ozmert, E.,Yalcin, S. S. Physical examination of breast-fed infants. Arch Pediatr Adolesc Med. 1997;151(4):429-30. | Study design
2578 | Zadik, Z.,Borondukov, E.,Zung, A.,Reifen, R. Adult height and weight of breast-fed and bottle-fed Israeli infants. J Pediatr Gastroenterol Nutr. 2003;37(4):462-7. | Included for systematic reviews not completed
2579 | Zadzinska E,Sitek A,Rosset I. Relationship between pre-natal factors, the perinatal environment, motor development in the first year of life and the timing of first deciduous tooth emergence. Ann Hum Biol. 2016;43:25-33. | Study design
2580 | Zaini, M. Z.,Lim, C. T.,Low, W. Y.,Harun, F. Factors affecting nutritional status of Malaysian primary school children. Asia Pac J Public Health. 2005;17(2):71-80. | Study design
2581 | Zamora, G.,Lutter, C. K.,Pena-Rosas, J. P. Using an equity lens in the implementation of interventions to protect, promote, and support optimal breastfeeding practices. J Hum Lact. 2015;31(1):21-5. | Study design, Dependent variable
2582 | Zarnani, A. H.,Modarres, Sh,Jadali, F.,Sabahi, F.,Moazzeni, S. M.,Vazirian, F. Role of rotaviruses in children with acute diarrhea in Tehran, Iran. Journal of Clinical Virology. 2004;29(3):189-193. | Study design, Health status
2583 | Zedan, M.,Nasef, N.,El-Bayoumy, M.,El-Assmy, M.,Attia, G.,Zedan, M.,AlWakeel, A.,Kandil, S.,Laimon, W.,Fouda, A. Does decline of lung function in wheezy infants justify the early start of controller medications?. Indian J Pediatr. 2012;79(9):1176-80. | Country
2584 | Zell, B. L. Breastfeeding as a community health imperative. Breastfeed Med. 2011;6:303-4. | Study design
2585 | Zetterstrom, R. Human milk and infant development. Foreword. Biol Neonate. 1998;74(2):80-3. | Study design
2586 | Zhang, J.,Himes, J. H.,Guo, Y.,Jiang, J.,Yang, L.,Lu, Q.,Ruan, H.,Shi, S. Birth weight, growth and feeding pattern in early infancy predict overweight/obesity status at two years of age: a birth cohort study of Chinese infants. PLoS One. 2013;8(6):e64542. | Included for systematic reviews not completed
2587 | Zhang, J.,Jiang, J.,Himes, J. H.,Zhang, J.,Liu, G.,Huang, X.,Guo, Y.,Shi, J.,Shi, S. Determinants of high weight gain and high BMI status in the first three months in urban Chinese infants. Am J Hum Biol. 2012;24(5):633-9. | Included for systematic reviews not completed
2588 | Zhang, S.,Liu, J.,Lo, E. C.,Chu, C. H. Dental caries status of Dai preschool children in Yunnan Province, China. BMC Oral Health. 2013;13:68. | Study design, Independent variable
2589 | Zheng, J. S.,Liu, H.,Li, J.,Chen, Y.,Wei, C.,Shen, G.,Zhu, S.,Chen, H.,Zhao, Y. M.,Huang, T.,Li, D. Exclusive breastfeeding is inversely associated with risk of childhood overweight in a large Chinese cohort. J Nutr. 2014;144(9):1454-9. | Included for systematic reviews not completed
2590 | Zheng, W.,Suzuki, K.,Shinohara, R.,Sato, M.,Yokomichi, H.,Yamagata, Z. Maternal smoking during pregnancy and growth in infancy: a covariance structure analysis. J Epidemiol. 2015;25(1):44-9. | Independent variable
2591 | Zhong, B. L.,Ding, J.,Chen, H. H.,Li, Y.,Xu, H. M.,Tong, J.,Wang, A. Q.,Tang, G. Z.,Zhu, J. S.,Yang, D. Q.,Liu, B.,Wang, Q.,Cheng, W. F.,Yin, E.,Xu, M. J.,Zhang, T.,Hu, T. M.,Feng, X. W.,Li, H.,Dan, T. Q.,Cheng, G. M.,Zhang, J. F.,Li, H. J.,Zhu, J. H. Depressive disorders among children in the transforming China: an epidemiological survey of prevalence, correlates, and service use. Depress Anxiety. 2013;30(9):881-92. | Study design
2592 | Zhou, S. J.,Baghurst, P.,Gibson, R. A.,Makrides, M. Home environment, not duration of breast-feeding, predicts intelligence quotient of children at four years. Nutrition. 2007;23(3):236-41. | Included for systematic reviews not completed
2593 | Zhou, S. J.,Sullivan, T.,Gibson, R. A.,Lonnerdal, B.,Prosser, C. G.,Lowry, D. J.,Makrides, M. Nutritional adequacy of goat milk infant formulas for term infants: a double-blind randomised controlled trial. Br J Nutr. 2014;111(9):1641-51. | Independent variable
2594 | Zhou, S. J.,Sullivan, T.,Gibson, R. A.,Makrides, M. How does goat milk infant formula compare to cow milk formula? A randomised controlled trial [conference abstract]. Journal of pediatric gastroenterology and nutrition. 2011;52:E208-e209. | Study design
2595 | Ziajka, S.,Zbikowski, Z. Characterization and properties of infant milk formulae with addition of enzymatically digested casein. Nahrung. 1986;30(3-4):413-4. | Study design, Independent variable
2596 | Ziegler, A. G.,Schmid, S.,Huber, D.,Hummel, M.,Bonifacio, E. Early infant feeding and risk of developing type 1 diabetes-associated autoantibodies. JAMA. 2003;290(13):1721-8. | Dependent variable
2597 | Ziegler, E. E.,Fields, D. A.,Chernausek, S. D.,Steenhout, P.,Grathwohl, D.,Jeter, J. M.,Nelson, S. E.,Haschke, F. Adequacy of Infant Formula With Protein Content of 1.6 g/100 kcal for Infants Between 3 and 12 Months. J Pediatr Gastroenterol Nutr. 2015;61(5):596-603. | Independent variable
2598 | Ziegler, E. E.,Jiang, T.,Romero, E.,Vinco, A.,Frantz, J. A.,Nelson, S. E. Cow’s milk and intestinal blood loss in late infancy. J Pediatr. 1999;135(6):720-6. | Independent variable, Dependent variable
2599 | Ziegler, E. E.,Nelson, S. E.,Jeter, J. M. Iron stores of breastfed infants during the first year of life. Nutrients. 2014;6(5):2023-34. | Independent variable
2600 | Ziegler, E.,Vanderhoof, J. A.,Petschow, B.,Mitmesser, S. H.,Stolz, S. I.,Harris, C. L.,Berseth, C. L. Term infants fed formula supplemented with selected blends of prebiotics grow normally and have soft stools similar to those reported for breast-fed infants. J Pediatr Gastroenterol Nutr. 2007;44(3):359-64. | Independent variable
2601 | Zielhuis, G. A.,Heuvelmans-Heinen, E. W.,Rach, G. H.,van den Broek, P. Environmental risk factors for otitis media with effusion in preschool children. Scand J Prim Health Care. 1989;7(1):33-8. | Included for systematic reviews not completed
2602 | Zive, M. M.,McKay, H.,Frank-Spohrer, G. C.,Broyles, S. L.,Nelson, J. A.,Nader, P. R. Infant-feeding practices and adiposity in 4-y-old Anglo- and Mexican-Americans. Am J Clin Nutr. 1992;55(6):1104-8. | Study design
2603 | Zollner, M. S.,Jorge, A. O. Candida spp. occurrence in oral cavities of breastfeeding infants and in their mothers’ mouths and breasts. Pesqui Odontol Bras. 2003;17(2):151-5. | Study design
2604 | Zoppi, G.,Ferrarini, G.,Rigolin, F.,Bogaerts, H.,Andre, F. E. Response to RIT 4237 oral rotavirus vaccine in breast-fed and formula-fed infants. Helv Paediatr Acta. 1986;41(3):203-8. | Group size
2605 | Zoppi, G.,Mantovanelli, F.,Gobio Casali, L.,Astolfi, R.,Cecchettin, M. Effects of the composition and caloric value of infant formulas on intake and hormone levels. J Pediatr Gastroenterol Nutr. 1986;5(5):756-61. | Group size
2606 | Zuccotti, G.,Vigano, A.,Cafarelli, L.,Pivetti, V.,Pogliani, L.,Puzzovio, M.,Mora, S. Longitudinal changes of bone ultrasound measurements in healthy infants during the first year of life: influence of gender and type of feeding. Calcif Tissue Int. 2011;89(4):312-7. | Dependent variable

6 U.S. Food and Drug Administration. Version 19 December 2013. Internet: https://www.fda.gov/Food/GuidanceRegulation/GuidanceDocumentsRegulatoryInformation/InfantFormula/ucm136118.htm#manufacture (accessed March 23, 2018).

7 Food and Agriculture Organization of the United Nations. World Health Organization. Codex Alimentarius. International Food Standards. Standard for infant formula and formulas for special medical purposes intended for infants. Codex Stan 72-1981. 2007.

8 In 1980 the Infant Formula Act was passed, and December 2015 was when the literature search occurred

9 U.S. Food and Drug Administration. Version 19 December 2013. Internet: https://www.fda.gov/Food/GuidanceRegulation/GuidanceDocumentsRegulatoryInformation/InfantFormula/ucm136118.htm#manufacture (accessed March 23, 2018).

10 Food and Agriculture Organization of the United Nations. World Health Organization. Codex Alimentarius. International Food Standards. Standard for infant formula and formulas for special medical purposes intended for infants. Codex Stan 72-1981. 2007.

11 United Nations Development Programme. Human Development Report 2014. Sustaining Human Progress: Reducing Vulnerabilities and Building Resilience. New York, 2014.