# List of abbreviations

Abbreviation: Full name
HbA1C: Hemoglobin A1C
NESR: Nutrition Evidence Systematic Review
TEC: Technical Expert Collaborative