# References of the articles included in the rapid reviews

1 Abuelezam NN, Cuevas AG, Galea S, Hawkins SS. Maternal Health Behaviors and Infant Health Outcomes Among Arab American and Non-Hispanic White Mothers in Massachusetts, 2012-2016. Public Health Rep. 2020;135(5):658–667. doi: 10.1177/0033354920941146.32805192
2 Belanoff CM, McManus BM, Carle AC, McCormick MC, Subramanian SV. Racial/ethnic variation in breastfeeding across the US: a multilevel analysis from the National Survey of Children’s Health, 2007. Matern Child Health J. 2012;16 Suppl 1:S14–26. doi: 10.1007/s10995-012-0991-1.22466719
3 Bramson L, Lee JW, Moore E, . Effect of early skin-to-skin mother--infant contact during the first 3 hours following birth on exclusive breastfeeding during the maternity hospital stay. Journal of Human Lactation. 2010;26(2):130–137. doi: 10.1177/0890334409355779.20110561
4 Buckman C, Diaz AL, Tumin D, Bear K. Parity and the Association Between Maternal Sociodemographic Characteristics and Breastfeeding. Breastfeed Med. 2020;15(7):443–452. doi: 10.1089/bfm.2019.0284.32456452
5 Campbell AG, Miranda PY. Breastfeeding Trends Among Very Low Birth Weight, Low Birth Weight, and Normal Birth Weight Infants. J Pediatr. 2018;200:71–78. doi: 10.1016/j.jpeds.2018.04.039.29784514
6 Carlin RF, Cornwell B, Mathews A, . Impact of Personal Social Network Types on Breastfeeding Practices in United States-Born Black and White Women. Breastfeed Med. 2021;16(10):807–813. doi: 10.1089/bfm.2021.0037.34009013
7 Carswell AL, Ward KD, Vander Weg MW, . Prospective associations of breastfeeding and smoking cessation among low-income pregnant women. Matern Child Nutr. 2018;14(4):e12622. doi: 10.1111/mcn.12622.29797420
8 Chen D, Fuell Wysong E, Li H, Perriera L, Furman L. Association of Postpartum Predischarge Depot-Medroxyprogesterone Acetate with In-Hospital Breastfeeding Initiation. Breastfeed Med. 2016;11:519–525. doi: 10.1089/bfm.2015.0164.27782765
9 Cheng ER, Taveras EM, Hawkins SS. Paternal Acculturation and Maternal Health Behaviors: Influence of Father’s Ethnicity and Place of Birth. J Womens Health (Larchmt). 2018;27(5):724–732. doi: 10.1089/jwh.2017.6439.29087779
10 Chung EK, Painter I, Sitcov K, Souter VD. Exclusive Breastfeeding in the Northwest: Disparities Related to Race/Ethnicity and Substance Use. Acad Pediatr. 2021;22:918–926. doi: 10.1016/j.acap.2021.09.016.34600112
11 Corsack C, Wallenborn JT, Harley KG, Eskenazi B. Parental Cohabitation and Breastfeeding Outcomes Among United States Adolescent Mothers. Breastfeed Med. 2022;17(1):72–78. doi: 10.1089/bfm.2021.0090.34958231
12 Dabritz HA, Hinton BG, Babb J. Maternal hospital experiences associated with breastfeeding at 6 months in a northern California county. J Hum Lact. 2010;26(3):274–285. doi: 10.1177/0890334410362222.20484659
13 Demirci JR, Sereika SM, Bogen D. Prevalence and predictors of early breastfeeding among late preterm mother-infant dyads. Breastfeed Med. 2013;8(3):277–285. doi: 10.1089/bfm.2012.0075.23199304
14 Fabiyi CA, Rankin K, Handler A. Association Between Breastfeeding Discouragement and Breastfeeding Behaviors. Jognn. 2021;50(5):568–582. doi: 10.1016/j.jogn.2021.04.010.34023316
15 Francescon J, Haile ZT, Kling D, Chertok I. Association Between WIC Enrollment and Exclusive Breastfeeding at 3 Months Postpartum Among Low-Income Mothers. J Am Osteopath Assoc. 2016;116(12):770–779. doi: 10.7556/jaoa.2016.152.27893143
16 Gertz B, DeFranco E. Predictors of breastfeeding non-initiation in the NICU. Matern Child Nutr. 2019;15(3):e12797. doi: 10.1111/mcn.12797.30767426
17 Glazer KB, Vieira L, Weber E, . COVID-19 pandemic-related change in racial and ethnic disparities in exclusive breastmilk feeding during the delivery hospitalization: a differences-in-differences analysis. BMC Pregnancy Childbirth. 2022;22(1):225. doi: 10.1186/s12884-022-04570-w.35305590
18 Gyllstrom ME, McCoy MB, Pezzini G, Atherly A. Leveraging Limited Resources Through Cross-Jurisdictional Sharing: Influences on Breastfeeding Rates. J Hum Lact. 2021;37(3):547–555. doi: 10.1177/0890334420963638.33030991
19 Haile ZT, Elmasry M, Chavan B, Azulay Chertok IR. Association Between Type of Health Professional at Birth and Exclusive Breastfeeding. Journal of Midwifery & Women’s Health. 2017;62(5):562–571. doi: 10.1111/jmwh.12657.
20 Hamilton WN, Tarasenko YN. Breastfeeding Practices in Georgia: Rural-Urban Comparison and Trend Analyses Based on 2004-2013 PRAMS Data. J Rural Health. 2020;36(1):17–26. doi: 10.1111/jrh.12382.31254310
21 Hawkins SS, Gillman MW, Shafer EF, Cohen BB. Acculturation and maternal health behaviors: findings from the Massachusetts birth certificate. Am J Prev Med. 2014;47(2):150–159. doi: 10.1016/j.amepre.2014.02.015.24951043
22 Hayes DK, Mitchell KM, Donohoe-Mather C, Zaha RL, Melcher C, Fuddy LJ. Predictors of exclusive breastfeeding at least 8 weeks among Asian and Native Hawaiian or other Pacific Islander race subgroups in Hawaii, 2004-2008. Matern Child Health J. 2014;18(5):1215–1223. doi: 10.1007/s10995-013-1355-1.24096640
23 Holland ML, Thevenent-Morrison K, Mittal M, Nelson A, Dozier AM. Breastfeeding and Exposure to Past, Current, and Neighborhood Violence. Matern Child Health J. 2018;22(1):82–91. doi: 10.1007/s10995-017-2357-1.28766093
24 Holmes AV, Auinger P, Howard CR. Combination feeding of breast milk and formula: evidence for shorter breast-feeding duration from the National Health and Nutrition Examination Survey. J Pediatr. 2011;159(2):186–191. doi: 10.1016/j.jpeds.2011.02.006.21429512
25 Hughes MM, Saiyed NS, Roesch PT, Masinter L, Sarup A. Local Disparities in Breastfeeding Initiation and Duration: A Cross-Sectional Population-Based Survey in Ten Chicago Community Areas. J Community Health. 2019;44(4):629–635. doi: 10.1007/s10900-018-00597-3.30569222
26 Jacobson LT, Twumasi-Ankrah P, Redmond ML, . Characteristics associated with breastfeeding behaviors among urban versus rural women enrolled in the Kansas WIC program. Matern Child Health J. 2015;19(4):828–839. doi: 10.1007/s10995-014-1580-2.25047788
27 Jolles DR, Montgomery TM, Blankstein Breman R, . Place of Birth Preferences and Relationship to Maternal and Newborn Outcomes Within the American Association of Birth Centers Perinatal Data Registry, 2007-2020. J Perinat Neonatal Nurs. 2022;36(2):150–160. doi: 10.1097/JPN.0000000000000647.35476769
28 Kachoria R, Oza-Frank R. Differences in breastfeeding initiation by maternal diabetes status and race, Ohio 2006-2011. Matern Child Health J. 2014;18(9):2226–2235. doi: 10.1007/s10995-014-1472-5.24682646
29 Kachoria R, Oza-Frank R. Factors associated with breastfeeding at discharge differ by maternal diabetes type. Diabet Med. 2014;31(10):1222–1229. doi: 10.1111/dme.12442.24654691
30 Kirksey K. A social history of racial disparities in breastfeeding in the United States. Soc Sci Med. 2021;289:114365. doi: 10.1016/j.socscimed.2021.114365.34592542
31 Kitsantas P, Gaffney KF, Kornides ML. Prepregnancy body mass index, socioeconomic status, race/ethnicity and breastfeeding practices. J Perinat Med. 2011;40(1):77–83. doi: 10.1515/JPM.2011.106.22044008
32 Kitsantas P, Pawloski LR. Maternal obesity, health status during pregnancy, and breastfeeding initiation and duration. J Matern Fetal Neonatal Med. 2010;23(2):135–141. doi: 10.3109/14767050903118270.19626567
33 Kortsmit K, Li R, Cox S, . Workplace Leave and Breastfeeding Duration Among Postpartum Women, 2016-2018. Am J Public Health. 2021;111(11):2036–2045. doi: 10.2105/AJPH.2021.306484.34678076
34 Krause KM, Lovelady CA, Østbye T. Predictors of breastfeeding in overweight and obese women: data from Active Mothers Postpartum (AMP). Matern Child Health J. 2011;15(3):367–375. doi: 10.1007/s10995-010-0667-7.20821042
35 Kummer L, Duke N, Davis L, Borowsky I. Association of Social and Community Factors with U.S. Breastfeeding Outcomes. Breastfeed Med. 2020;15(10):646–654. doi: 10.1089/bfm.2020.0083.32856942
36 Lee HJ, Elo IT, McCollum KF, Culhane JF. Racial/Ethnic Differences in Breastfeeding Initiation and Duration Among Low-income, Inner-city Mothers. Soc Sci Q. 2009;90(5):1251–1271. doi: 10.1111/j.1540-6237.2009.00656.x.20160902
37 Liu J, Smith MG, Dobre MA, Ferguson JE. Maternal obesity and breast-feeding practices among white and black women. Obesity (Silver Spring). 2010;18(1):175–182. doi: 10.1038/oby.2009.182.19521347
38 Lundquist J, Xu Z, Barfield W, Elo I. Do black-white racial disparities in breastfeeding persist in the military community? Matern Child Health J. 2015;19(2):419–427. doi: 10.1007/s10995-014-1524-x.24894729
39 Lynch S, Bethel J, Chowdhury N, Moore JB. Rural and urban breastfeeding initiation trends in low-income women in North Carolina from 2003 to 2007. J Hum Lact. 2012;28(2):226–232. doi: 10.1177/0890334411430086.22275048
40 Ma P, Magnus JH. Exploring the concept of positive deviance related to breastfeeding initiation in black and white WIC enrolled first time mothers. Matern Child Health J. 2012;16(8):1583–1593. doi: 10.1007/s10995-011-0852-3.21822964
41 Marshall C, Gavin L, Bish C, . WIC participation and breastfeeding among White and Black mothers: data from Mississippi. Matern Child Health J. 2013;17(10):1784–1792. doi: 10.1007/s10995-012-1198-1.23203317
42 Masho SW, Cha S, Morris MR. Prepregnancy obesity and breastfeeding noninitiation in the United States: an examination of racial and ethnic differences. Breastfeed Med. 2015;10(5):253–262. doi: 10.1089/bfm.2015.0006.25898171
43 McKinney CO, Hahn-Holbrook J, Chase-Lansdale PL, . Racial and Ethnic Differences in Breastfeeding. Pediatrics. 2016;138(2):e20152388. doi: 10.1542/peds.2015-2388.27405771
44 Mercier RJ, Burcher TA, Horowitz R, Wolf A. Differences in Breastfeeding Among Medicaid and Commercially Insured Patients: A Retrospective Cohort Study. Breastfeed Med. 2018;13(4):286–291. doi: 10.1089/bfm.2017.0228.29634340
45 Morrow AL, McClain J, Conrey SC, . Breastfeeding Disparities and Their Mediators in an Urban Birth Cohort of Black and White Mothers. Breastfeed Med. 2021;16(6):452–462. doi: 10.1089/bfm.2020.0327.33733869
46 Nguyen T, Dennison BA, Fan W, Xu C, Birkhead GS. Variation in Formula Supplementation of Breastfed Newborn Infants in New York Hospitals. Pediatrics. 2017;140(1):e20170142. doi: 10.1542/peds.2017-0142.28759408
47 Ogbuanu C, Glover S, Probst J, Liu J, Hussey J. The effect of maternity leave length and time of return to work on breastfeeding. Pediatrics. 2011;127(6):e1414–1427. doi: 10.1542/peds.2010-0459.21624878
48 Orozco J, Echeverria SE, Armah SM, Dharod JM. Household Food Insecurity, Breastfeeding, and Related Feeding Practices in US Infants and Toddlers: Results From NHANES 2009-2014. J Nutr Educ Behav. 2020;52(6):588–594. doi: 10.1016/j.jneb.2020.02.011.32276879
49 Pithia N, Dong A, Grogan T, Govardhan S, Calkins KL. Race and Ethnicity and Exclusive Breastfeeding Success. Breastfeed Med. 2021;16(5):402–406. doi: 10.1089/bfm.2020.0333.33635147
50 Safon CB, Heeren TC, Kerr SM, . Disparities in Breastfeeding Among U.S. Black Mothers: Identification of Mechanisms. Breastfeed Med. 2021;16(2):140–149. doi: 10.1089/bfm.2020.0310.33539248
51 Shafer EF, Hawkins SS. The Impact of Sex of Child on Breastfeeding in the United States. Matern Child Health J. 2017;21(11):2114–2121. doi: 10.1007/s10995-017-2326-8.28755041
52 Sipsma HL, Magriples U, Divney A, Gordon D, Gabzdyl E, Kershaw T. Breastfeeding behavior among adolescents: initiation, duration, and exclusivity. J Adolesc Health. 2013;53(3):394–400. doi: 10.1016/j.jadohealth.2013.04.005.23725911
53 Sparks PJ. Rural-urban differences in breastfeeding initiation in the United States. J Hum Lact. 2010;26(2):118–129. doi: 10.1177/0890334409352854.20032310
54 Sparks PJ. Racial/ethnic differences in breastfeeding duration among WIC-eligible families. Womens Health Issues. 2011;21(5):374–382. doi: 10.1016/j.whi.2011.03.002.21565528
55 Stevens DR, Taylor SN, Roberts JR, . Breastfeeding Initiation as Related to the Interaction of Race/Ethnicity and Maternal Diabetes. Breastfeed Med. 2019;14(9):630–639. doi: 10.1089/bfm.2019.0065.31364862
56 Tanda R, Chertok IRA, Haile ZT, Chavan BB. Factors That Modify the Association of Maternal Postpartum Smoking and Exclusive Breastfeeding Rates. Breastfeed Med. 2018;13(9):614–621. doi: 10.1089/bfm.2018.0079.30285471
57 Thompson LA, Zhang S, Black E, . The association of maternal pre-pregnancy body mass index with breastfeeding initiation. Matern Child Health J. 2013;17(10):1842–1851. doi: 10.1007/s10995-012-1204-7.23247667
58 Walker LO, Cheng HR, Brown A. Birth Outcomes of Hispanic Women and Risks or Strengths Associated with Ethnicity and Texas Border Residence. Jognn. 2014;43(4):422–434. doi: 10.1111/1552-6909.12467.24947021
59 Wallenborn JT, Chambers GJ, Masho SW. The Role of Paternity Acknowledgment in Breastfeeding Noninitiation. J Hum Lact. 2018;34(4):737–744. doi: 10.1177/0890334417743209.29161532
60 Wallenborn JT, Chambers GJ, Scialli A, Orekoya O, Masho SW. Interracial couples and breastfeeding initiation in the United States. Prev Med. 2019;120:140–143. doi: 10.1016/j.ypmed.2019.01.015.30685317
61 Wallenborn JT, Graves WC, Masho SW. Breastfeeding Initiation in Mothers with Repeat Cesarean Section: The Impact of Marital Status. Breastfeed Med. 2017;12:227–232. doi: 10.1089/bfm.2016.0205.28358578
62 Wallenborn JT, Ihongbe T, Rozario S, Masho SW. Knowledge of Breastfeeding Recommendations and Breastfeeding Duration: A Survival Analysis on Infant Feeding Practices II. Breastfeed Med. 2017;12:156–162. doi: 10.1089/bfm.2016.0170.28394658
63 Weiser TM, Lin M, Garikapaty V, Feyerharm RW, Bensyl DM, Zhu BP. Association of maternal smoking status with breastfeeding practices: Missouri, 2005. Pediatrics. 2009;124(6):1603–1610. doi: 10.1542/peds.2008-2711.19917583
64 White MJ, Kay MC, Truong T, . Racial and Ethnic Differences in Maternal Social Support and Relationship to Mother-Infant Health Behaviors. Acad Pediatr. 2022;22:1429–1436. doi: 10.1016/j.acap.2022.02.008.35227910
65 Whitley MD, Ro A, Choi B. Low job control and racial disparities in breastfeeding. J Occup Environ Med. 2022;64:e482–491. doi: 10.1097/JOM.0000000000002591.35688422
66 Whitley MD, Ro A, Palma A. Work, race and breastfeeding outcomes for mothers in the United States. PLoS One. 2021;16(5):e0251125. doi: 10.1371/journal.pone.0251125.33951094
67 Wiener RC, Sambamoorthi U, Hayes SE, Azulay Chertok IR. Association of Breastfeeding and the Federal Poverty Level: National Survey of Family Growth, 2011-2013. Epidemiol Res Int. 2016;2016:9783704. doi: 10.1155/2016/9783704.27019750
68 Wouk K, Stuebe AM, Meltzer-Brody S. Postpartum Mental Health and Breastfeeding Practices: An Analysis Using the 2010-2011 Pregnancy Risk Assessment Monitoring System. Matern Child Health J. 2017;21(3):636–647. doi: 10.1007/s10995-016-2150-6.27449655
69 Yourkavitch J, Kane JB, Miles G. Neighborhood Disadvantage and Neighborhood Affluence: Associations with Breastfeeding Practices in Urban Areas. Matern Child Health J. 2018;22(4):546–555. doi: 10.1007/s10995-017-2423-8.29294250
70 Yu SM, Lin SC, Adirim T. Selected Health Status Measures of Children from US Immigrant Families. ISRN Pediatr. 2013;2013:164757. doi: 10.1155/2013/164757.23936667
71 Zhang Q, Chen C, Xue H, Park K, Wang Y. Revisiting the Relationship between WIC Participation and Breastfeeding among Low-Income Children in the U.S. after the 2009 WIC Food Package Revision. Food Policy. 2021;101:102089. doi: 10.1016/j.foodpol.2021.102089.34054198
72 Alexander A, Dowling D, Furman L. What do pregnant low-income women say about breastfeeding? Breastfeed Med. 2010;5(1):17–23. doi: 10.1089/bfm.2009.0034.20043706
73 Asiodu IV, Waters CM, Dailey DE, Lee KA, Lyndon A. Breastfeeding and use of social media among first-time African American mothers. J Obstet Gynecol Neonatal Nurs. 2015;44(2):268–278. doi: 10.1111/1552-6909.12552.
74 Asiodu IV, Waters CM, Dailey DE, Lyndon A. Infant Feeding Decision-Making and the Influences of Social Support Persons Among First-Time African American Mothers. Matern Child Health J. 2017;21(4):863–872. doi: 10.1007/s10995-016-2167-x.27565664
75 Avery A, Zimmermann K, Underwood PW, Magnus JH. Confident commitment is a key factor for sustained breastfeeding. Birth. 2009;36(2):141–148. doi: 10.1111/j.1523-536X.2009.00312.x.19489808
76 Ayers BL, Purvis RS, Bogulski CA, . “It’s Okay With Our Culture but We’re in a Different Place and We Have to Show Respect”: Marshallese Migrants and Exclusive Breastfeeding Initiation. J Hum Lact. 2022;38:732–739. doi: 10.1177/08903344221077133.35337206
77 Bader LR, Ward J, Fouts HN, Jaekel J. Infant Care Practices among Resettled Refugee Mothers from East and Central Africa. Children (Basel). 2020;7(6):63. doi: 10.3390/children7060063.32560348
78 Barbosa CE, Masho SW, Carlyle KE, Mosavel M. Factors Distinguishing Positive Deviance Among Low-Income African American Women: A Qualitative Study on Infant Feeding. J Hum Lact. 2017;33(2):368–378. doi: 10.1177/0890334416673048.27881731
79 Bartick M, Reyes C. Las dos cosas: an analysis of attitudes of latina women on non-exclusive breastfeeding. Breastfeed Med. 2012;7(1):19–24.doi: 10.1089/bfm.2011.0039.22007765
80 Biediger-Friedman L, Crixell SH, Silva M, Markides BR, Smith KS. User-centered Design of a Texas WIC App: A Focus Group Investigation. Am J Health Behav. 2016;40(4):461–471. doi: 10.5993/AJHB.40.4.8.27338993
81 Bookhart LH, Joyner AB, Lee K, Worrell N, Jamieson DJ, Young MF. Moving Beyond Breastfeeding Initiation: A Qualitative Study Unpacking Factors That Influence Infant Feeding at Hospital Discharge Among Urban, Socioeconomically Disadvantaged Women. J Acad Nutr Diet. 2021;121(9):1704–1720. doi: 10.1016/j.jand.2021.02.005.33715976
82 Carlin RF, Mathews A, Oden R, Moon RY. The Influence of Social Networks and Norms on Breastfeeding in African American and Caucasian Mothers: A Qualitative Study. Breastfeed Med. 2019;14(9):640–647. doi: 10.1089/bfm.2019.0044.31433206
83 Chopel A, Soto D, Joiner B, . Multilevel Factors Influencing Young Mothers’ Breastfeeding: A Qualitative CBPR Study. J Hum Lact. 2019;35(2):301–317. doi: 10.1177/0890334418812076.30517824
84 Cottrell BH, Detman LA. Breastfeeding concerns and experiences of African American mothers. MCN Am J Matern Child Nurs. 2013;38(5):297–304. doi: 10.1097/NMC.0b013e31829a5606.23958620
85 Davis C, Villalobos AVK, Turner MM, Long S, Lapinski MK. Racism and Resistance: A Qualitative Study of Bias As a Barrier to Breastfeeding. Breastfeed Med. 2021;16(6):471–480. doi: 10.1089/bfm.2020.0307.33784475
86 Deubel TF, Miller EM, Hernandez I, Boyer M, Louis-Jacques A. Perceptions and Practices of Infant Feeding among African American Women. Ecol Food Nutr. 2019;58(4):301–316. doi: 10.1080/03670244.2019.1598977.31035771
87 DeVane-Johnson S, Giscombe CW, Williams R, nd F, C T. A Qualitative Study of Social, Cultural, and Historical Influences on African American Women’s Infant-Feeding Practices. J Perinat Educ. 2018;27(2):71–85. doi: 10.1891/1058-1243.27.2.71.30863005
88 Fabiyi C, Peacock N, Hebert-Beirne J, Handler A. A Qualitative Study to Understand Nativity Differences in Breastfeeding Behaviors Among Middle-Class African American and African-Born Women. Matern Child Health J. 2016;20(10):2100–2111. doi: 10.1007/s10995-016-2029-6.27334637
89 Felder TM, Cayir E, Nkwonta CA, Tucker CM, Harris EH, Jackson JR. A Mixed-Methods Feasibility Study of Breastfeeding Attitudes among Southern African Americans. West J Nurs Res. 2022;44(1):50–65. doi: 10.1177/01939459211045431.34554033
90 Fischer TP, Olson BH. A qualitative study to understand cultural factors affecting a mother’s decision to breast or formula feed. J Hum Lact. 2014;30(2):209–216. doi: 10.1177/0890334413508338.24186645
91 Furman LM, Banks EC, North AB. Breastfeeding among high-risk inner-city African-American mothers: a risky choice? Breastfeed Med. 2013;8(1):58–67. doi: 10.1089/bfm.2012.0012.22823328
92 Glassman ME, McKearney K, Saslaw M, Sirota DR. Impact of breastfeeding self-efficacy and sociocultural factors on early breastfeeding in an urban, predominantly Dominican community. Breastfeed Med. 2014;9(6):301–307. doi: 10.1089/bfm.2014.0015.24902047
93 Gross RS, Brown NM, Mendelsohn AL, Katzow MW, Arana MM, Messito MJ. Maternal Stress and Infant Feeding in Hispanic Families Experiencing Poverty. Acad Pediatr. 2022;22(1):71–79. doi: 10.1016/j.acap.2021.04.022.33940204
94 Gross RS, Mendelsohn AL, Arana MM, Messito MJ. Food Insecurity During Pregnancy and Breastfeeding by Low-Income Hispanic Mothers. Pediatrics. 2019;143(6):e20184113. doi: 10.1542/peds.2018-4113.31088893
95 Gross TT, Davis M, Anderson AK, Hall J, Hilyard K. Long-Term Breastfeeding in African American Mothers. J Hum Lact. 2017;33(1):128–139. doi: 10.1177/0890334416680180.28061039
96 Haughton J, Gregorio D, Pérez-Escamilla R. Factors associated with breastfeeding duration among Connecticut Special Supplemental Nutrition Program for Women, Infants, and Children (WIC) participants. J Hum Lact. 2010;26(3):266–273. doi: 10.1177/0890334410365067.20689103
97 Henshaw EJ, Cooper MA, Jaramillo M, Lamp JM, Jones AL, Wood TL. “Trying to Figure Out If You’re Doing Things Right, and Where to Get the Info”: Parents Recall Information and Support Needed During the First 6 weeks Postpartum. Matern Child Health J. 2018;22(11):1668–1675. doi: 10.1007/s10995-018-2565-3.29978309
98 Hill N, Hunt E, Hyrkäs K. Somali immigrant women’s health care experiences and beliefs regarding pregnancy and birth in the United States. J Transcult Nurs. 2012;23(1):72–81. doi: 10.1177/1043659611423828.22052095
99 Hinson TD, Skinner AC, Lich KH, Spatz DL. Factors That Influence Breastfeeding Initiation Among African American Women. J Obstet Gynecol Neonatal Nurs. 2018;47(3):290–300. doi: 10.1016/j.jogn.2018.02.007.
100 Hohl S, Thompson B, Escareño M, Duggan C. Cultural Norms in Conflict: Breastfeeding Among Hispanic Immigrants in Rural Washington State. Matern Child Health J. 2016;20(7):1549–1557. doi: 10.1007/s10995-016-1954-8.27021068
101 Jefferson UT, Bloom TL, Lewis KR. Infant Feeding Exposure and Personal Experiences of African American Mothers. Breastfeed Med. 2021;16(2):124–130. doi: 10.1089/bfm.2020.0073.32865430
102 Jefferson UT, Reed AE, Rabbitte M. African American Mothers’ Decision to Discontinue Breastfeeding and Switch to Formula. West J Nurs Res. 2022;44(1):15–22. doi: 10.1177/01939459211041164.34496680
103 Johnson AM, Kirk R, Muzik M. Overcoming Workplace Barriers: A Focus Group Study Exploring African American Mothers’ Needs for Workplace Breastfeeding Support. J Hum Lact. 2015;31(3):425–433. doi: 10.1177/0890334415573001.25714345
104 Johnson AM, Kirk R, Rooks AJ, Muzik M. Enhancing Breastfeeding Through Healthcare Support: Results from a Focus Group Study of African American Mothers. Matern Child Health J. 2016;20(Suppl 1):92–102. doi: 10.1007/s10995-016-2085-y.27449776
105 Joshi A, Trout KE, Aguirre T, Wilhelm S. Exploration of factors influencing initiation and continuation of breastfeeding among Hispanic women living in rural settings: a multi-methods study. Rural Remote Health. 2014;14(3):2955. doi: 10.22605/RRH2955.25170852
106 Kadakia A, Joyner B, Tender J, Oden R, Moon RY. Breastfeeding in African Americans may not depend on sleep arrangement: a mixed-methods study. Clin Pediatr (Phila). 2015;54(1):47–53. doi: 10.1177/0009922814547565.25139664
107 Kaufman L, Deenadayalan S, Karpati A. Breastfeeding ambivalence among low-income African American and Puerto Rican women in north and central Brooklyn. Matern Child Health J. 2010;14(5):696–704. doi: 10.1007/s10995-009-0499-5.19644744
108 Kim JH, Fiese BH, Donovan SM. Breastfeeding is Natural but Not the Cultural Norm: A Mixed-Methods Study of First-Time Breastfeeding, African American Mothers Participating in WIC. J Nutr Educ Behav. 2017;49(7 Suppl 2):S151–161.e151. doi: 10.1016/j.jneb.2017.04.003.28689552
109 Kulka TR, Jensen E, McLaurin S, . Community based participatory research of breastfeeding disparities in African American women. Infant Child Adolesc Nutr. 2011;3(4):233–239. doi: 10.1177/1941406411413918.23326622
110 Lebron CN, Agosto Y, Guzman T, . A qualitative study of cognitive, behavioral, and environmental influences on Hispanic mothers’ early childhood feeding practices. Appetite. 2021;164:105268. doi: 10.1016/j.appet.2021.105268.33864860
111 Lee A, Brann L. Influence of Cultural Beliefs on Infant Feeding, Postpartum and Childcare Practices among Chinese-American Mothers in New York City. J Community Health. 2015;40(3):476–483. doi: 10.1007/s10900-014-9959-y.25331609
112 Lee S, Bai YK, You SB. Ecological Factors Influencing Breastfeeding Decisions among Korean Immigrant Mothers in America. J Child Fam Stud. 2018;27(3):928–943. doi: 10.1007/s10826-017-0927-x.
113 Lee YI, Baker S. Understanding the Racialized Breastfeeding Experiences Among Black Millennials. Breastfeed Med. 2021;16(6):481–486. doi: 10.1089/bfm.2020.0305.33960828
114 Lewallen LP, Street DJ. Initiating and sustaining breastfeeding in african american women. J Obstet Gynecol Neonatal Nurs. 2010;39(6):667–674. doi: 10.1111/j.1552-6909.2010.01196.x.
115 Lindsay AC, Wallington SF, Greaney ML, Hasselman MH, Tavares Machado MM, Mezzavilla RS. Brazilian Immigrant Mothers’ Beliefs and Practices Related to Infant Feeding: A Qualitative Study. J Hum Lact. 2017;33(3):595–605. doi: 10.1177/0890334416676267.27881729
116 Lutenbacher M, Karp SM, Moore ER. Reflections of Black Women Who Choose to Breastfeed: Influences, Challenges and Supports. Matern Child Health J. 2016;20(2):231–239. doi: 10.1007/s10995-015-1822-y.26496988
117 Ma A, Merçon-Vargas EA, Chambers BD, Nyambe M, Williams TA. Context of Breastfeeding among Latina Mothers using a Social-ecological Approach: An Exploratory Study. J Public Health Issues Pract. 2018;2:124. doi: 10.33790/jphip1100124.31414077
118 McGlothen KS, Cleveland LM, Gill SL. “I’m Doing the Best That I Can for Her”: Infant-Feeding Decisions of Mothers Receiving Medication-Assisted Treatment for an Opioid Use Disorder. Journal of Human Lactation. 2018;34(3):535–542. doi: 10.1177/0890334417745521.29324188
119 Munn AC, Newman SD, Phillips SM, Mueller M, Taylor SN. Factors Influencing Southeastern U.S. Mothers’ Participation in Baby-Friendly Practices: A Mixed-Methods Study. J Hum Lact. 2018;34(4):821–834. doi: 10.1177/0890334417750143.29432703
120 Muse MM, Morris JE, Dodgson JE. An Intergenerational Exploration of Breastfeeding Journeys Through the Lens of African American Mothers and Grandmothers. J Hum Lact. 2021;37(2):289–300. doi: 10.1177/0890334421999304.33715481
121 Obeng CS, Emetu RE, Curtis TJ. African-American Women’s Perceptions and Experiences About Breastfeeding. Front Public Health. 2015;3:273. doi: 10.3389/fpubh.2015.00273.26734597
122 Obeng CS, Larson E. Parents’ motivations and views on combining breast milk and formula. International Journal of Child Health & Human Development. 2014;7(1):31–35.
123 Owens N, Carter SK, Nordham CJ, Ford JA. Neutralizing the Maternal Breast: Accounts of Public Breastfeeding by African American Mothers. J Fam Issues. 2018;39(2):430–450. doi: 10.1177/0192513X16650229.
124 Peacock-Chambers E, Dicks K, Sarathy L, Brown AA, Boynton-Jarrett R. Perceived Maternal Behavioral Control, Infant Behavior, and Milk Supply: A Qualitative Study. J Dev Behav Pediatr. 2017;38(6):401–408. doi: 10.1097/DBP.0000000000000455.28570412
125 Pearlman Shapiro M, Avila K, Levi EE. Breastfeeding and contraception counseling: a qualitative study. BMC Pregnancy Childbirth. 2022;22(1):154. doi: 10.1186/s12884-022-04451-2.35216562
126 Racine EF, Frick KD, Strobino D, Carpenter LM, Milligan R, Pugh LC. How motivation influences breastfeeding duration among low-income women. J Hum Lact. 2009;25(2):173–181. doi: 10.1177/0890334408328129.19176705
127 Robinson A, Davis M, Hall J, Lauckner C, Anderson AK. It Takes an E-Village: Supporting African American Mothers in Sustaining Breastfeeding Through Facebook Communities. J Hum Lact. 2019;35(3):569–582. doi: 10.1177/0890334419831652.30889373
128 Robinson K, VandeVusse L. Exploration of African-American women’s infant feeding choices. J Natl Black Nurses Assoc. 2009;20(2):32–37.20364724
129 Robinson K, VandeVusse L, Foster J. Reactions of Low-Income African American Women to Breastfeeding Peer Counselors. J Obstet Gynecol Neonatal Nurs. 2016;45(1):62–70. doi: 10.1016/j.jogn.2015.10.011.
130 Robinson KM, VandeVusse L. African American women’s infant feeding choices: prenatal breast-feeding self-efficacy and narratives from a black feminist perspective. J Perinat Neonatal Nurs. 2011;25(4):320–328. doi: 10.1097/JPN.0b013e31821072fb.22071615
131 Schindler-Ruwisch J, Roess A, Robert RC, Napolitano M. Limitations of Workplace Lactation Support: The Case for DC WIC Recipients. J Hum Lact. 2020;36(1):59–63. doi: 10.1177/0890334419887369.31815588
132 Schindler-Ruwisch J, Roess A, Robert RC, . Determinants of Breastfeeding Initiation and Duration Among African American DC WIC Recipients: Perspectives of Recent Mothers. Womens Health Issues. 2019;29(6):513–521. doi: 10.1016/j.whi.2019.07.003.31409521
133 Shipp GM, Weatherspoon LJ, Norman GS, Alexander GL, Kelleher D, Kerver JM. Understanding Factors Influencing Breastfeeding Outcomes in a Sample of African American Women. Matern Child Health J. 2022;26(4):853–862. doi: 10.1007/s10995-021-03261-w.34637064
134 Sloand E, Lowe V, Pennington A, Rose L. Breastfeeding Practices and Opinions of Latina Mothers in an Urban Pediatric Office: A Focus Group Study. J Pediatr Health Care. 2018;32(3):236–244. doi: 10.1016/j.pedhc.2017.11.001.29361391
135 Spencer B, Wambach K, Domain EW. African American Women’s Breastfeeding Experiences: Cultural, Personal, and Political Voices. Qual Health Res. 2015;25(7):974–987. doi: 10.1177/1049732314554097.25288408
136 Steinman L, Doescher M, Keppel GA, . Understanding infant feeding beliefs, practices and preferred nutrition education and health provider approaches: an exploratory study with Somali mothers in the USA. Matern Child Nutr. 2010;6(1):67–88. doi: 10.1111/j.1740-8709.2009.00185.x.20055931
137 Teich AS, Barnett J, Bonuck K. Women’s Perceptions of Breastfeeding Barriers in Early Postpartum Period: A Qualitative Analysis Nested in Two Randomized Controlled Trials. Breastfeed Med. 2014;9(1):9–15. doi: 10.1089/bfm.2013.0063.24304033
138 Textor L, Tiedje K, Yawn B. Mexican and Somali immigrant breastfeeding initiation and counseling: a qualitative study of practices. Minn Med. 2013;96(12):46–50.
139 Tucker CM, Wilson EK, Samandari G. Infant feeding experiences among teen mothers in North Carolina: Findings from a mixed-methods study. Int Breastfeed J. 2011;6:14. doi: 10.1186/1746-4358-6-14.21955654
140 Vaughn LM, Ireton C, Geraghty SR, . Sociocultural Influences on the Determinants of Breast-feeding by Latina Mothers in the Cincinnati Area. Fam Community Health. 2010;33(4):318–328. doi: 10.1097/FCH.0b013e3181f3b2be.20736758
141 Wambach K, Domian EW, Page-Goertz S, Wurtz H, Hoffman K. Exclusive Breastfeeding Experiences among Mexican American Women. J Hum Lact. 2016;32(1):103–111. doi: 10.1177/0890334415599400.26289059
142 Woods Barr AL, Austin DA, Smith JL, Schafer EJ. “…[T]his is What We are Missing”: The Value of Communicating Infant Feeding Information Across Three Generations of African American Women. J Hum Lact. 2021;37(2):279–288. doi: 10.1177/0890334421995078.33632016
143 Woods Barr AL, Miller E, Smith JL, Cummings SM, Schafer EJ. #EveryGenerationMatters: Intergenerational Perceptions of Infant Feeding Information and Communication Among African American Women. Breastfeed Med. 2021;16(2):131–139. doi: 10.1089/bfm.2020.0308.33591228
144 Little EE, Cioffi CC, Bain L, Legare CH, Hahn-Holbrook J. An Infant Carrier Intervention and Breastfeeding Duration: A Randomized Controlled Trial. Pediatrics. 2021;148(1):e2020049717. doi: 10.1542/peds.2020-049717.34193622
145 Griffin LB, López JD, Ranney ML, Macones GA, Cahill AG, Lewkowitz AK. Effect of Novel Breastfeeding Smartphone Applications on Breastfeeding Rates. Breastfeed Med. 2021;16(8):614–623. doi: 10.1089/bfm.2021.0012.33826418
146 Gurtcheff SE, Turok DK, Stoddard G, Murphy PA, Gibson M, Jones KP. Lactogenesis after early postpartum use of the contraceptive implant: a randomized controlled trial. Obstet Gynecol. 2011;117(5):1114–1121. doi: 10.1097/AOG.0b013e3182165ee8.21508750
147 Lewkowitz AK, López JD, Carter EB, . Impact of a novel smartphone application on low-income, first-time mothers’ breastfeeding rates: a randomized controlled trial. Am J Obstet Gynecol MFM. 2020;2(3):100143. doi: 10.1016/j.ajogmf.2020.100143.33345878
148 Lewkowitz AK, López JD, Werner EF, . Effect of a Novel Smartphone Application on Breastfeeding Rates Among Low-Income, First-Time Mothers Intending to Exclusively Breastfeed: Secondary Analysis of a Randomized Controlled Trial. Breastfeed Med. 2021;16(1):59–67. doi: 10.1089/bfm.2020.0240.33085510
149 Palacios C, Campos M, Gibby C, Meléndez M, Lee JE, Banna J. Effect of a Multi-Site Trial using Short Message Service (SMS) on Infant Feeding Practices and Weight Gain in Low-Income Minorities. J Am Coll Nutr. 2018;37(7):605–613. doi: 10.1080/07315724.2018.1454353.29708471
150 Pezley L, Tussing-Humphreys L, Koenig MD, . Feasibility of a Web-Based Intervention to Prevent Perinatal Depression and Promote Human Milk Feeding: Randomized Pilot Trial. JMIR Form Res. 2022;6(5):e32226. doi: 10.2196/32226.35503244
151 Caine VA, Smith M, Beasley Y, Brown HL. The impact of prenatal education on behavioral changes toward breast feeding and smoking cessation in a healthy start population. J Natl Med Assoc. 2012;104(5–6):258–264. doi: 10.1016/S0027-9684(15)30159-0.22973675
152 Campbell LA, Wan J, Speck PM, Hartig MT. Women, Infant and Children (WIC) peer counselor contact with first time breastfeeding mothers. Public Health Nurs. 2014;31(1):3–9. doi: 10.1111/phn.12055.24387771
153 Cloutier MM, Wiley JF, Kuo CL, Cornelius T, Wang Z, Gorin AA. Outcomes of an early childhood obesity prevention program in a low-income community: a pilot, randomized trial. Pediatr Obes. 2018;13(11):677–685. doi: 10.1111/ijpo.12458.30156058
154 Edmunds LS, Lee FF, Eldridge JD, Sekhobo JP. Outcome Evaluation of the You Can Do It Initiative to Promote Exclusive Breastfeeding Among Women Enrolled in the New York State WIC Program by Race/Ethnicity. J Nutr Educ Behav. 2017;49(7 Suppl 2):S162–S168.e161. doi: 10.1016/j.jneb.2017.05.350.28689553
155 Gabbe PT, Reno R, Clutter C, . Improving Maternal and Infant Child Health Outcomes with Community-Based Pregnancy Support Groups: Outcomes from Moms2B Ohio. Matern Child Health J. 2017;21(5):1130–1138. doi: 10.1007/s10995-016-2211-x.28074311
156 Gleason S, Wilkin MK, Sallack L, Whaley SE, Martinez C, Paolicelli C. Breastfeeding Duration Is Associated With WIC Site-Level Breastfeeding Support Practices. J Nutr Educ Behav. 2020;52(7):680–687. doi: 10.1016/j.jneb.2020.01.014.32171671
157 Gross SM, Resnik AK, Cross-Barnet C, Nanda JP, Augustyn M, Paige DM. The differential impact of WIC peer counseling programs on breastfeeding initiation across the state of Maryland. J Hum Lact. 2009;25(4):435–443. doi: 10.1177/0890334409342070.19652195
158 Gross SM, Resnik AK, Nanda JP, . Early postpartum: a critical period in setting the path for breastfeeding success. Breastfeed Med. 2011;6(6):407–412.doi: 10.1089/bfm.2010.0089.21453122
159 Harari N, Rosenthal MS, Bozzi V, . Feasibility and acceptability of a text message intervention used as an adjunct tool by WIC breastfeeding peer counsellors: The LATCH pilot. Matern Child Nutr. 2018;14(1):e12488. doi: 10.1111/mcn.12488.28766913
160 Harris-Luna ML, Badr LK. Pragmatic Trial to Evaluate the Effect of a Promotora Telephone Intervention on the Duration of Breastfeeding. J Obstet Gynecol Neonatal Nurs. 2018;47(6):738–748. doi: 10.1016/j.jogn.2018.09.001.
161 Jenkins LA, Barnes K, Latter A, Edwards RA. Examining the Baby Café Model and Mothers’ Breastfeeding Duration, Meeting of Goals, and Exclusivity. Breastfeed Med. 2020;15(5):331–334.doi: 10.1089/bfm.2019.0179.32216632
162 Lewkowitz AK, López JD, Stein RI, . Effect of a Home-Based Lifestyle Intervention on Breastfeeding Initiation Among Socioeconomically Disadvantaged African American Women with Overweight or Obesity. Breastfeed Med. 2018;13(6):418–425. doi: 10.1089/bfm.2018.0006.29912571
163 Li K, Wen M, Reynolds M, Zhang Q. WIC Participation and Breastfeeding after the 2009 WIC Revision: A Propensity Score Approach. Int J Environ Res Public Health. 2019;16(15):2645. doi: 10.3390/ijerph16152645.31344937
164 Lovera D, Sanderson M, Bogle ML, Vela Acosta MS. Evaluation of a breastfeeding peer support program for fathers of Hispanic participants in a Texas special supplemental nutrition program for women, infants, and children. J Am Diet Assoc. 2010;110(11):1696–1702. doi: 10.1016/j.jada.2010.08.001.21034883
165 Lutenbacher M, Elkins T, Dietrich MS. Using Community Health Workers to Improve Health Outcomes in a Sample of Hispanic Women and Their Infants: Findings from a Randomized Controlled Trial. Hisp Health Care Int. 2022:15404153221107680. doi: 10.1177/15404153221107680.
166 Lutenbacher M, Elkins T, Dietrich MS, Riggs A. The Efficacy of Using Peer Mentors to Improve Maternal and Infant Health Outcomes in Hispanic Families: Findings from a Randomized Clinical Trial. Matern Child Health J. 2018;22(Suppl 1):92–104. doi: 10.1007/s10995-018-2532-z.
167 Martinez-Brockman JL, Harari N, Pérez-Escamilla R. Lactation Advice through Texting Can Help: An Analysis of Intensity of Engagement via Two-Way Text Messaging. J Health Commun. 2018;23(1):40–51. doi: 10.1080/10810730.2017.1401686.29236569
168 Martinez-Brockman JL, Harari N, Segura-Pérez S, Goeschel L, Bozzi V, Pérez-Escamilla R. Impact of the Lactation Advice Through Texting Can Help (LATCH) Trial on Time to First Contact and Exclusive Breastfeeding among WIC Participants. J Nutr Educ Behav. 2018;50(1):33–42.e31. doi: 10.1016/j.jneb.2017.09.001.29325660
169 Mersky JP, Janczewski CE, Plummer Lee C, Gilbert RM, McAtee C, Yasin T. Home Visiting Effects on Breastfeeding and Bedsharing in a Low-Income Sample. Health Educ Behav. 2021;48(4):488–495. doi: 10.1177/1090198120964197.33078655
170 Reeder JA, Joyce T, Sibley K, Arnold D, Altindag O. Telephone peer counseling of breastfeeding among WIC participants: a randomized controlled trial. Pediatrics. 2014;134(3):e700–709. doi: 10.1542/peds.2013-4146.25092936
171 Reifsnider E, McCormick DP, Cullen KW, . Randomized Controlled Trial to Prevent Infant Overweight in a High-Risk Population. Acad Pediatr. 2018;18(3):324–333. doi: 10.1016/j.acap.2017.12.007.29277462
172 Rotheram-Fuller E, Swendeman D, Becker K, . Adapting Current Strategies to Implement Evidence-Based Prevention Programs for Paraprofessional Home Visiting. Prev Sci. 2017;18(5):590–599. doi: 10.1007/s11121-017-0787-z.28451922
173 Rotheram-Fuller EJ, Swendeman D, Becker KD, . Replicating Evidence-Based Practices with Flexibility for Perinatal Home Visiting by Paraprofessionals. Matern Child Health J. 2017;21(12):2209–2218. doi: 10.1007/s10995-017-2342-8.28755042
174 Sandy JM, Anisfeld E, Ramirez E. Effects of a prenatal intervention on breastfeeding initiation rates in a Latina immigrant sample. J Hum Lact. 2009;25(4):404–411. doi: 10.1177/0890334409337308.19487705
175 Tussing-Humphreys L, Thomson JL, Goodman M, Landry A. Enhanced vs Standard Parents as Teacher Curriculum on Factors Related to Infant Feeding among African American Women. South Med J. 2019;112(10):512–519. doi: 10.14423/smj.0000000000001024.31583410
176 Ventura AK, Silva Garcia K, Meza M, Rodriguez E, Martinez CE, Whaley SE. Promoting Responsive Bottle-Feeding Within WIC: Evaluation of a Policy, Systems, and Environmental Change Approach. J Acad Nutr Diet. 2022;122(1):99–109.e102. doi: 10.1016/j.jand.2021.05.003.34090838
177 Washio Y, Humphreys M, Colchado E, . Incentive-based Intervention to Maintain Breastfeeding Among Low-income Puerto Rican Mothers. Pediatrics. 2017;139(3):e20163119. doi: 10.1542/peds.2016-3119.28167511
178 Chiasson MA, Findley SE, Sekhobo JP, . Changing WIC changes what children eat. Obesity (Silver Spring). 2013;21(7):1423–1429. doi: 10.1002/oby.20295.23703806
179 Ahlers-Schmidt CR, Okut H, Dowling J. Impact of Prenatal Education on Breastfeeding Initiation Among Low-Income Women. Am J Health Promot. 2020;34(8):919–922. doi: 10.1177/0890117120925342.32406242
180 Ahluwalia IB, Morrow B, D’Angelo D, Li R. Maternity care practices and breastfeeding experiences of women in different racial and ethnic groups: Pregnancy Risk Assessment and Monitoring System (PRAMS). Matern Child Health J. 2012;16(8):1672–1678. doi: 10.1007/s10995-011-0871-0.21847676
181 Beauregard JL, Nelson JM, Li R, Perrine CG, Hamner HC. Maternity Care Practices and Breastfeeding Intentions at One Month Among Low-Income Women. Pediatrics. 2022;149(4):e2021052561. doi: 10.1542/peds.2021-052561.35253063
182 Bonuck K, Stuebe A, Barnett J, Labbok MH, Fletcher J, Bernstein PS. Effect of Primary Care Intervention on Breastfeeding Duration and Intensity. Am J Public Health. 2014;104:S119–127. doi: 10.2105/AJPH.2013.301360.24354834
183 Burnham L, Knapp R, Bugg K, . Mississippi CHAMPS: Decreasing Racial Inequities in Breastfeeding. Pediatrics. 2022;149(2):e2020030502. doi: 10.1542/peds.2020-030502.35104360
184 Chae SY, Chae MH, Kandula S, Winter RO. Promoting improved social support and quality of life with the CenteringPregnancy(®) group model of prenatal care. Arch Womens Ment Health. 2017;20(1):209–220. doi: 10.1007/s00737-016-0698-1.27988822
185 Chapman DJ, Morel K, Bermúdez-Millán A, Young S, Damio G, Pérez-Escamilla R. Breastfeeding education and support trial for overweight and obese women: a randomized trial. Pediatrics. 2013;131(1):e162–170. doi: 10.1542/peds.2012-0688.23209111
186 Disantis KI, Collins BN, McCoy ACS. Associations among breastfeeding, smoking relapse, and prenatal factors in a brief postpartum smoking intervention. Acta Obstet Gynecol Scand. 2010;89(4):582–586. doi: 10.3109/00016341003678435.20235894
187 Edwards RC, Thullen MJ, Korfmacher J, Lantos JD, Henson LG, Hans SL. Breastfeeding and complementary food: randomized trial of community doula home visiting. Pediatrics. 2013;132 S160–166. doi: 10.1542/peds.2013-1021P.24187119
188 Efrat MW, Esparza S, Mendelson SG, Lane CJ. The effect of lactation educators implementing a telephone-based intervention among low-income Hispanics: A randomised trial. Health Educ J. 2015;74(4):424–441. doi: 10.1177/0017896914542666.26941454
189 Ekambaram M, Irigoyen MM, Paoletti A, Siddiqui I. Impact of a Baby-Friendly-Aligned Pacifier Policy on Pacifier Use at 1 Month of Age. Acad Pediatr. 2019;19(7):808–814. doi: 10.1016/j.acap.2019.02.002.30772504
190 Grassley JS, Sauls DJ. Evaluation of the Supportive Needs of Adolescents during Childbirth Intrapartum Nursing Intervention on Adolescents’ Childbirth Satisfaction and Breastfeeding Rates. JOGNN: Journal of Obstetric, Gynecologic & Neonatal Nursing. 2012;41(1):33–44. doi: 10.1111/j.1552-6909.2011.01310.x.
191 Gross RS, Mendelsohn AL, Gross MB, Scheinmann R, Messito MJ. Randomized Controlled Trial of a Primary Care-Based Child Obesity Prevention Intervention on Infant Feeding Practices. J Pediatr. 2016;174:171–177.e172. doi: 10.1016/j.jpeds.2016.03.060.27113376
192 Gruber KJ, Cupito SH, Dobson CF. Impact of Doulas on Healthy Birth Outcomes. Journal of Perinatal Education. 2013;22(1):49–58. doi: 10.1891/0730-0832.22.1.49.24381478
193 Hans SL, Edwards RC, Zhang Y. Randomized Controlled Trial of Doula-Home-Visiting Services: Impact on Maternal and Infant Health. Matern Child Health J. 2018;22(Suppl 1):105–113. doi: 10.1007/s10995-018-2537-7.29855838
194 Hemingway S, Forson-Dare Z, Ebeling M, Taylor SN. Racial Disparities in Sustaining Breastfeeding in a Baby-Friendly Designated Southeastern United States Hospital: An Opportunity to Investigate Systemic Racism. Breastfeed Med. 2021;16(2):150–155. doi: 10.1089/bfm.2020.0306.33539272
195 Hopkinson J, Konefal Gallagher M. Assignment to a hospital-based breastfeeding clinic and exclusive breastfeeding among immigrant Hispanic mothers: a randomized, controlled trial. J Hum Lact. 2009;25(3):287–296. doi: 10.1177/0890334409335482.19436060
196 Howell EA, Bodnar-Deren S, Balbierz A, Parides M, Bickell N. An intervention to extend breastfeeding among black and Latina mothers after delivery. Am J Obstet Gynecol. 2014;210(3):239.e231–235. doi: 10.1016/j.ajog.2013.11.028.
197 Jung S, Nobari TZ, Whaley SE. Breastfeeding Outcomes Among WIC-Participating Infants and Their Relationships to Baby-Friendly Hospital Practices. Breastfeed Med. 2019;14(6):424–431. doi: 10.1089/bfm.2019.0004.31084434
198 Kao JC, Johnson JE, Todorova R, Zlotnick C. The Positive Effect of a Group Intervention to Reduce Postpartum Depression on Breastfeeding Outcomes in Low-Income Women. Int J Group Psychother. 2015;65(3):445–458. doi: 10.1521/ijgp.2015.65.3.445.26076207
199 Keenan-Devlin LS, Hughes-Jones JY, Borders AEB. Clinically integrated breastfeeding peer counseling and breastfeeding outcomes. J Perinatol. 2021;41(8):2095–2103. doi: 10.1038/s41372-021-01096-5.34035450
200 Kelly B, Irigoyen M, Pomerantz S, Mondesir M, Isaza-Brando N. Swaddling and Infant Sleeping Practices. Journal of Community Health. 2017;42(1):10–14. doi: 10.1007/s10900-016-0219-1.27393144
201 Kettrey HH, Steinka-Fry KT. Effects of March of Dimes Supportive Pregnancy Care on Maternal and Infant Health Across Diverse Patient Populations: a Quasi-Experimental Multi-Site Pilot Study. Prev Sci. 2020;21(3):293–307. doi: 10.1007/s11121-019-01083-5.31907756
202 Klima C, Norr K, Vonderheid S, Handler A. Introduction of CenteringPregnancy in a public health clinic. J Midwifery Womens Health. 2009;54(1):27–34. doi: 10.1016/j.jmwh.2008.05.008.19114236
203 Knutson J, Butler J. Providing Equitable Postpartum Breastfeeding Support at an Urban Academic Hospital. Nurs Womens Health. 2022;26(3):184–193. doi: 10.1016/j.nwh.2022.03.002.35398044
204 Kozhimannil KB, Attanasio LB, Hardeman RR, O’Brien M. Doula care supports near-universal breastfeeding initiation among diverse, low-income women. J Midwifery Womens Health. 2013;58(4):378–382. doi: 10.1111/jmwh.12065.23837663
205 Langellier BA, Pia Chaparro M, Whaley SE. Social and institutional factors that affect breastfeeding duration among WIC participants in Los Angeles County, California. Matern Child Health J. 2012;16(9):1887–1895. doi: 10.1007/s10995-011-0937-z.22205423
206 Lau JD, Zhu Y, Vora S. An Evaluation of a Perinatal Education and Support Program to Increase Breastfeeding in a Chinese American Community. Matern Child Health J. 2021;25(2):214–220. doi: 10.1007/s10995-020-03016-z.33196922
207 Linares AM, Cartagena D, Rayens MK. Las Dos Cosas Versus Exclusive Breastfeeding: A Culturally and Linguistically Exploratory Intervention Study in Hispanic Mothers Living in Kentucky. J Pediatr Health Care. 2019;33(6):e46–e56. doi: 10.1016/j.pedhc.2019.07.009.31655788
208 Martinez NG, Strohbach A, Hu F, Yee LM. “Real-world” effect of a peer counselor on breastfeeding outcomes in an urban prenatal clinic in the United States. BMC Pregnancy Childbirth. 2020;20(1):671. doi: 10.1186/s12884-020-03360-6.33160332
209 Merewood A, Bugg K, Burnham L, . Addressing Racial Inequities in Breastfeeding in the Southern United States. Pediatrics. 2019;143(2):e20181897. doi: 10.1542/peds.2018-1897.30659064
210 Moon RY, Mathews A, Joyner BL, Oden RP, He J, McCarter R. Impact of a Randomized Controlled Trial to Reduce Bedsharing on Breastfeeding Rates and Duration for African-American Infants. J Community Health. 2017;42(4):707–715. doi: 10.1007/s10900-016-0307-2.28064421
211 Nobari TZ, Jiang L, Wang MC, Whaley SE. Baby-Friendly Hospital Initiative and Breastfeeding Among WIC-Participating Infants in Los Angeles County. J Hum Lact. 2017;33(4):677–683. doi: 10.1177/0890334417716118.28793204
212 Nommsen-Rivers LA, Mastergeorge AM, Hansen RL, Cullum AS, Dewey KG. Doula care, early breastfeeding outcomes, and breastfeeding status at 6 weeks postpartum among low-income primiparae. J Obstet Gynecol Neonatal Nurs. 2009;38(2):157–173. doi: 10.1111/j.1552-6909.2009.01005.x.
213 Patberg E, Young M, Archer S, . Postpartum Contraceptive Use and Other Reproductive Health Outcomes Among CenteringPregnancy Group Prenatal Care Participants. J Womens Health (Larchmt). 2021;30(7):990–996. doi: 10.1089/jwh.2019.8241.33052781
214 Petrova A, Ayers C, Stechna S, Gerling JA, Mehta R. Effectiveness of exclusive breastfeeding promotion in low-income mothers: a randomized controlled study. Breastfeed Med. 2009;4(2):63–69. doi: 10.1089/bfm.2008.0126.19239405
215 Pitcock N, Pineda K, Ossinova N, Yoder L. Education and Support: Tilting the Scale Toward Exclusive Breastfeeding. Clinical Lactation. 2021;12(2):83–90.doi: 10.1891/CLINLACT-D-20-00026.
216 Pugh LC, Serwint JR, Frick KD, . A randomized controlled community-based trial to improve breastfeeding rates among urban low-income mothers. Acad Pediatr. 2010;10(1):14–20. doi: 10.1016/j.acap.2009.07.005.19854119
217 Qureshey E, Louis-Jacques AF, Abunamous Y, Curet S, Quinones J. Impact of a Formal Lactation Curriculum for Residents on Breastfeeding Rates Among Low-Income Women. J Perinat Educ. 2020;29(2):83–89. doi: 10.1891/J-PE-D-18-00018.32308357
218 Robertson B, Aycock DM, Darnell LA. Comparison of centering pregnancy to traditional care in Hispanic mothers. Matern Child Health J. 2009;13(3):407–414. doi: 10.1007/s10995-008-0353-1.18465216
219 Rosen-Carole C, Halterman J, Baldwin CD, . Prenatal Provider Breastfeeding Toolkit: Results of a Pilot to Increase Women’s Prenatal Breastfeeding Support, Intentions, and Outcomes. J Hum Lact. 2022;38(1):64–74. doi: 10.1177/08903344211008797.33823702
220 Schreck PK, Solem K, Wright T, Schulte C, Ronnisch KJ, Szpunar S. Both Prenatal and Postnatal Interventions Are Needed to Improve Breastfeeding Outcomes in a Low-Income Population. Breastfeed Med. 2017;12:142–148. doi: 10.1089/bfm.2016.0131.28394657
221 Scott A, Vowell-Johnson K, Addington C, Adams BS, Pennington O. Intent to Breastfeed and Evaluation of Culturally Sensitive Education in a Migrant Pacific Islander Population. Clinical Lactation. 2019;10(1):22–28. doi: 10.1891/2158-0782.10.1.22.
222 Sebastian RA, Coronado E, Otero MD, McKinney CR, Ramos MM. Associations Between Maternity Care Practices and 2-Month Breastfeeding Duration Vary by Race, Ethnicity, and Acculturation. Matern Child Health J. 2019;23(6):858–867. doi: 10.1007/s10995-018-02711-2.30659460
223 Stuebe AM, Bonuck K, Adatorwovor R, Schwartz TA, Berry DC. A Cluster Randomized Trial of Tailored Breastfeeding Support for Women with Gestational Diabetes. Breastfeed Med. 2016;11(10):504–513. doi: 10.1089/bfm.2016.0069.27782758
224 Watt TT, Appel L, Lopez V, Flores B, Lawhon B. A Primary Care-Based Early Childhood Nutrition Intervention: Evaluation of a Pilot Program Serving Low-Income Hispanic Women. J Racial Ethn Health Disparities. 2015;2(4):537–547. doi: 10.1007/s40615-015-0102-2.26863560
225 Wilhelm SL, Aguirre TM, Koehler AE, Rodehorst TK. Evaluating motivational interviewing to promote breastfeeding by rural Mexican-American mothers: the challenge of attrition. Issues Compr Pediatr Nurs. 2015;38(1):7–21. doi: 10.3109/01460862.2014.971977.25373565
226 Dennison BA, FitzPatrick E, Zhang W, Nguyen T. New York State Paid Family Leave Law Associated with Increased Breastfeeding Among Black Women. Breastfeed Med. 2022;17:618–626. doi: 10.1089/bfm.2022.0015.35475735
227 Hamad R, Modrek S, White JS. Paid Family Leave Effects on Breastfeeding: A Quasi-Experimental Study of US Policies. Am J Public Health. 2019;109(1):164–166. doi: 10.2105/AJPH.2018.304693.30359107
228 Hawkins SS, Stern AD, Gillman MW. Do state breastfeeding laws in the USA promote breast feeding? J Epidemiol Community Health. 2013;67(3):250–256. doi: 10.1136/jech-2012-201619.23087383
229 Langellier BA, Chaparro MP, Wang MC, Koleilat M, Whaley SE. The new food package and breastfeeding outcomes among women, infants, and children participants in Los Angeles County. Am J Public Health. 2014;104 Suppl 1(Suppl 1):S112–118. doi: 10.2105/AJPH.2013.301330.24354843
230 Reat AM, Crixell SH, Friedman BJ, Von Bank JA. Comparison of Food Intake Among Infants and Toddlers Participating in a South Central Texas WIC Program Reveals Some Improvements After WIC Package Changes. Matern Child Health J. 2015;19(8):1834–1841. doi: 10.1007/s10995-015-1697-y.25656719
231 Smith-Gagen J, Hollen R, Tashiro S, Cook DM, Yang W. The association of state law to breastfeeding practices in the US. Matern Child Health J. 2014;18(9):2034–2043. doi: 10.1007/s10995-014-1449-4.24535146
232 Smith-Gagen J, Hollen R, Walker M, Cook DM, Yang W. Breastfeeding laws and breastfeeding practices by race and ethnicity. Womens Health Issues. 2014;24(1):e11–19. doi: 10.1016/j.whi.2013.11.001.24439936
233 Wilde P, Wolf A, Fernandes M, Collins A. Food-package assignments and breastfeeding initiation before and after a change in the Special Supplemental Nutrition Program for Women, Infants, and Children. Am J Clin Nutr. 2012;96(3):560–566. doi: 10.3945/ajcn.112.037622.22836028
234 Kapinos KA, Bullinger L, Gurley-Calvez T. Lactation Support Services and Breastfeeding Initiation: Evidence from the Affordable Care Act. Health Serv Res. 2017;52(6):2175–2196. doi: 10.1111/1475-6773.12598.27861824