# Chapter 5 Summary

## Summary statements

The NESR team answered the rapid review questions (Key Question 2 and Key Question 3) with the following summary statements.

#### Key Question 2 What factors are associated with racial and/or ethnic disparities in human milk feeding in the United States?

##### NIMHD framework: individual level – biological domain

Evidence suggests that pre-pregnancy obesity, compared to a normal pre-pregnancy BMI, may be associated with lower human milk feeding initiation among White, but not Black, mothers. There is not enough consistent evidence to determine whether maternal BMI is associated with racial and ethnic disparities in human milk feeding duration.

Evidence suggests that postpartum depression may not be associated with the relationship between race and ethnicity in human milk feeding duration among Black, Hispanic, and White mothers.

There is not enough consistent evidence among the small number of studies to determine whether mode of delivery is associated with racial and ethnic disparities in human milk feeding initiation.

Evidence that suggests that gestational age may not be associated with the relationship between race and ethnicity (Black, Hispanic, White) and human milk feeding initiation.

##### NIMHD framework: individual level – behavioral domain

Evidence indicates that smoking is not associated with racial and ethnic disparities in human milk feeding initiation among Black, Hispanic, and White mothers. Evidence suggests that postpartum smoking may not be associated with racial and ethnic disparities in human milk feeding durations among Black, Hispanic, and White mothers.

##### NIMHD framework: individual level – sociocultural environment domain

Evidence suggests that maternal nativity may be associated with the relationship between race and human milk feeding initiation among Black and White mothers, such that foreign-born Black mothers initiated human milk feeding at higher rates than U.S.-born Black mothers, while associations were inconsistent for White mothers.

Evidence suggests that maternal age may not be associated with racial and ethnic disparities in human milk feeding initiation or duration.

Evidence indicates that maternal education is not associated with racial and ethnic disparities in human milk feeding initiation among Black, Hispanic, and White mothers. Evidence suggests that lower levels of maternal education may be associated with shorter human milk feeding duration for Black mothers compared to White mothers.

Evidence suggests that income and income-related factors may not be associated with the relationship between race and ethnicity and human milk feeding initiation among Black, Hispanic, and White mothers. There is not enough consistent evidence to determine whether associations between race and ethnicity and human milk feeding duration vary by income and income-related factors.

Evidence suggests that parity may not be associated with racial and ethnic disparities in human milk feeding initiation and duration among Black, Hispanic, and White mothers.

##### NIMHD framework: interpersonal level – biological domain

There is not enough consistent evidence among the small number of studies to determine whether birth weight is associated with racial and ethnic disparities in human milk feeding duration.

##### NIMHD framework: interpersonal level – behavioral domain

Evidence suggests that employment or aspects of employment may not be associated with disparities in human milk feeding initiation between Black, Other, and White mothers. There is not enough consistent evidence among the heterogeneous variables related to employment to determine whether employment is associated with disparities in human milk feeding duration between Black and White mothers.

##### NIMHD framework: interpersonal level – sociocultural environment domain

Evidence suggests that marital status may not be associated with racial and ethnic disparities in human milk feeding initiation. There is not enough consistent evidence among the small number of studies to determine whether marital status is associated with racial and ethnic disparities in human milk feeding duration.

There is not enough consistent evidence among the small number of studies to determine whether paternal race and ethnicity is associated with racial and ethnic disparities in human milk feeding initiation.

There is not enough consistent evidence among the small number of studies to determine whether social support is associated with racial and ethnic disparities in human milk feeding duration.

##### NIMHD framework: community level – physical/built environment domain

There is not enough consistent evidence among the small number of studies to determine whether urbanicity is associated with racial and ethnic disparities in human milk feeding initiation.

Evidence suggests that prenatal or postpartum WIC participation may not be associated with the relationship between race and ethnicity and human milk feeding duration among Black, Hispanic, and White mothers. There is not enough consistent evidence to determine whether WIC participation is associated with racial and ethnic disparities in human milk feeding initiation.

##### NIMHD framework: community level – health care system domain

Evidence suggests that baby-friendly hospital practices may not be associated with the relationship between race and ethnicity and human milk feeding initiation for Black, Hispanic, and White mothers. There is not enough consistent evidence among the small number of studies to determine whether baby-friendly hospital practices are associated with racial and ethnic disparities in human milk feeding duration.

There is not enough consistent evidence among the small number of studies to determine whether NICU admission is associated with racial and ethnic disparities in human milk feeding initiation.

#### Key Question 3 What interventions, programs, initiatives, and policies impact racial and/or ethnic disparities in human milk feeding in the United States, and do impacts vary across different racial and/or ethnic, socioeconomic, and geographic groups?

##### NIMHD framework: individual level – behavioral domain

There is not enough evidence to develop a summary statement for individual-behavioral interventions, programs, initiatives, and policies.

##### NIMHD framework: individual level – health care system domain

Evidence suggests that individual-health care system interventions focused on technology may not impact human milk feeding outcomes in racially and/or ethnically diverse populations. However, this evidence is limited by the small number of studies identified, relatively small sample sizes, marked heterogeneity in the interventions and populations assessed, and several risk of bias concerns.

##### NIMHD framework: community level – physical/built environment domain

Evidence suggests that community-physical/built environment interventions and programs, including home visiting programs delivered by community health workers or peer mentors, and certain WIC programs and services, may be associated with longer durations of any or exclusive human milk feeding among women who were predominantly Hispanic or Black/African American and of lower socioeconomic status. The evidence was limited by risk of bias concerns across all study designs.

##### NIMHD framework: community level – health care system domain

Evidence suggests that community-health care system interventions, programs, initiatives, and policies, including Baby-Friendly hospital practices and group-based programs, may be associated with more favorable human milk feeding outcomes in populations predominantly consisting of individuals from U.S. racial and ethnic minority groups. Among the interventions, programs, initiatives, and policies assessed, the evidence is most consistent for Baby-Friendly hospital practices. The evidence is predominantly generalizable to women who are Hispanic, Latina, or Black, or African American and, apart from studies that examined Baby-Friendly hospital practices, to women with a lower socioeconomic status. The evidence was limited by several risk of bias concerns across all study designs.

##### NIMHD framework: societal level – behavioral domain

Evidence suggests that societal-behavioral policies, including paid family leave laws and laws supporting human milk feeding, may be associated with more favorable human milk feeding outcomes in populations predominantly consisting of individuals from U.S. racial and ethnic minority groups. However, the policies and laws assessed across all the studies were heterogenous, the number of studies available for each category of policy or law was relatively small, and there was some inconsistency in results by racial and/or ethnic group. The evidence was further limited by several risk of bias concerns.

##### NIMHD framework: societal level – health care system domain

There is not enough evidence to develop a summary statement for societal-health care system interventions, programs, initiatives, and policies.

## Summary tables and figures

Table 35 Summary table of quantitative results for the rapid review question, what factors are associated with racial and/or ethnic disparities in human milk feeding in the United States? (Key Question 2)

| HMF Initiation | HMF Duration (any or exclusive)
May be associated | Maternal nativity; Pre-pregnancy obesity | Maternal education
May not be associated | Baby-friendly hospital practices; Employment; Gestational age; Income; Marital status; Maternal age; Maternal education; Parity; Smoking | Maternal age; Maternal nativity; Parity; Postpartum depression; Smoking; WIC participation

The following factors were identified, but not enough evidence or not enough consistent evidence was found to form summary statements: mode of delivery, diabetes, hypertension, gestational weight gain, attitudes and beliefs, intention to breastfeed, having a breastfeeding plan, perceived control, information or knowledge of breastfeeding recommendation, early feeding practices, total stress factors, substance use (not smoking) during pregnancy, acculturation, insurance and contraception, birth weight, child sex, infant health, violence exposure, household environment-related variables, including insufficient privacy/space in home, unstable housing before birth, number of people living with mother, recent move prior to pregnancy, rooms in the residence, coresident father, coresident grandparent, paternal education, paternity acknowledgement, paternal race and ethnicity, paternal nativity, maternal or paternal grandmother breastfed their own child, social support, mother/partner as primary caretakers, subjective norms, coronavirus pandemic, geographic location (mothers dwelling in the United States-Mexico border versus mothers who are not dwelling in the United States-Mexico Border), military affiliation, neighborhood characteristics, urbanicity, neonatal intensive care unit (NICU), breastfeeding information from hospital staff, type of birth attendant, prenatal care, hospital level of perinatal care, labor anesthesia, medical conditions or labor/delivery complications, maternity leave length.

Table 36 Summary table of qualitative results for the rapid review question, what factors are associated with racial and/or ethnic disparities in human milk feeding in the United States? (Key Question 2)^a^ a Themes where the overwhelming majority of references were positive or negative were placed into those categories. Otherwise they were placed in the both column. .

Positive breastfeeding themes | Negative breastfeeding themes | Both positive and negative breastfeeding themes
Breastfeeding beliefs, knowledge, and experiences:; - Breastfeeding being convenient or easy; - Health benefits; Perseverance; Previous breastfeeding experience | Breastfeeding beliefs, knowledge, and experiences:; - Breast milk is nutritionally unreliable or insufficient; - Body image; - Fear; - Infant age; - Infant attachment; - Life demands and stress; - Lifestyle; - Not knowing if infant was adequately fed; - Time and responsibilities; Breastfeeding in public; Cost of hospital lactation services; Exposure to formula feeding; Formula feeding beliefs; - Convenience and ease of formula feeding; - Health benefits of formula feeding; Health issues; Historical context; Hospital practices; Infant preferences; Introduction to solid foods; Lack of support after hospital discharge; Physical breastfeeding problems; Returning to work; Sexualized view of breasts and breastfeeding; Sharing care of infant | Breastfeeding beliefs, knowledge, and experiences:; - Breastfeeding attitudes; - Cost of breast or formula feeding; - Knowledge; Community resources and support:; - Breastfeeding resources; - Community social support; Confidence; Cultural beliefs, practices, and norms; Exposure to breastfeeding; Formula feeding beliefs:; - Attitudes; Home environment; Information and support from health care providers; Intention to breastfeed or formula feed; Maternity leave and breastfeeding laws; Social support:; - Social support from family; - Social support from partner; - Social support from social network; Work environment

Figure 12 Summary table of results organized using the NIMHD research framework, for the rapid review question, what interventions, programs, initiatives, and policies impact racial and/or ethnic disparities in human milk feeding in the United States, and do impacts vary across different racial and/or ethnic, socioeconomic, and geographic groups? (Key Question 3)^a^ a Abbreviations: ACA, Affordable Care Act; HMF, human milk feeding; WIC, Special Supplemental Nutrition Program for Women, Infants, and Children

Summary table of results organized using the NIMHD research framework, for the rapid review question, what interventions, programs, initiatives, and policies impact racial and/or ethnic disparities in human milk feeding in the United States, and do impacts vary across different racial and/or ethnic, socioeconomic, and geographic groups? (Key Question 3)

| NIMHD Level
NIMHD Domain | Individual | Interpersonal | Community | Societal
Biological
Behavioral | Not enough evidence; 1 article:; - Ergonomic infant carrier (1) | | | May be associated with more favorable HMF outcomes in populations predominantly consisting of individuals from U.S. racial and ethnic minority groups.^b^; b The policies and laws assessed across all the studies were heterogenous, the number of studies available for each category of policy or law was relatively small, and there was some inconsistency in results by racial and ethnic group. The evidence was further limited by several risk of bias concerns.; 9 articles:; - WIC package revision (4); - Paid family leave laws (2); - State laws pertaining to BF (3)
Physical/Built environment | | | May be associated with longer durations of any or exclusive HMF among women who were predominantly Hispanic or Black/African American and of lower socioeconomic status.^c^; c The evidence was limited by risk of bias concerns across all study designs.; 27 articles:; - WIC programs and services (12); - Community health worker and peer educator/mentor home visiting programs (11); - Other (4)
Sociocultural environment
Health care system | May not impact HMF outcomes in populations predominantly consisting of individuals from U.S. racial and ethnic minority groups.^d^; d This evidence is limited by the small number of studies identified, relatively small sample sizes, marked heterogeneity in the interventions and populations assessed, and several risk of bias concerns.; 6 articles:; - Technology-focused interventions, e.g., educational smart phone application, automated text messages, web-based education (5); - Other (1) | | May be associated with more favorable HMF outcomes in populations predominantly consisting of individuals from U.S. racial and ethnic minority groups. The evidence is predominantly generalizable to women who are Hispanic, Latina, or Black, or African American and, apart from studies that examined Baby-Friendly hospital practices, to women with a lower socioeconomic status.^e^; e Among the interventions, programs, initiatives, and policies assessed, the evidence is most consistent for Baby-Friendly hospital practices. The evidence was limited by several risk of bias concerns across all study designs.; 48 articles:; - Baby-Friendly hospital practices (11); - Group-based prenatal/postpartum interventions (11); - Individual BF education, counseling, support (22); - Other (3) | Not enough evidence; 1 article:; - ACA-mandated lactation support (1)

## Research recommendations

To address the gaps in and limitations of this body of evidence on racial and ethnic disparities in human milk feeding, several research recommendations have been identified:

1. Conduct research on factors that may be associated with human milk feeding disparities:
  a. using mediation or moderation analyses, particularly for factors that did not have enough studies to draw a summary statement
  b. in a broader range of racial and/or ethnic groups, such as with individuals who are American Indian/Alaska Native, Asian, and Native Hawaiian and other Pacific Islander
2. Compare qualitative breastfeeding themes between racial and/or ethnic groups to identify themes that are unique to specific racial and/or ethnic groups
3. Quantitatively compare qualitative themes between racial and/or ethnic groups to identify similarities or differences across groups, due to few factors/themes overlapping between qualitative and quantitative studies
4. Conduct research on interventions, programs, initiatives, and/or policies to address racial and/or ethnic disparities in human milk feeding in:
  a. a broader range of racial and/or ethnic groups, such as with individuals who are American Indian/Alaska Native, Native Hawaiian, or Pacific Islander
  b. individuals who live in rural areas
5. Provide information on how race and/or ethnicity were defined and operationalized in the studies (e.g., social construct, biological construct)
6. Provide information on the specific racial and/or ethnic groups included in “other” categories
7. Examine grey literature to further identify factors or themes related to racial and/or ethnic disparities in human milk feeding, which may present additional perspectives compared to what is found in peer-reviewed literature