# Chapter 4 What interventions, programs, initiatives, and policies impact racial and/or ethnic disparities in human milk feeding in the United States, and do impacts vary across different racial and/or ethnic, socioeconomic, and geographic groups? (Key Question 3)

## Plain-language summary

#### What is the question?

What interventions, programs, initiatives, and policies impact racial and ethnic disparities in human milk feeding in the United States, and do impacts vary across different racial and/or ethnic, socioeconomic, and geographic groups?

#### Why was this question asked?

To summarize evidence on interventions, programs, initiatives, and policies that may address racial and/or ethnic disparities in human milk feeding, in order to inform FNS communication and program guidance on this topic.

#### How was this question answered?

The Nutrition Evidence Systematic Review (NESR) team conducted a rapid review to answer this question.

#### What was the population of interest?

The population of interest is parent-infant dyads living in the United States.

#### How up-to-date is this rapid review?

This review searched for studies published between January 2009 and June 2022.

#### What evidence was found and what is the answer to the question?

The rapid review includes 91 articles. The articles were organized based on the National Institute on Minority Health and Health Disparities (NIMHD) research framework.

##### NIMHD framework: individual level – behavioral domain

- [underlined: What evidence was found]: This section includes one article. The study found that giving an infant carrier to Latina individuals living in a low-income community had positive impacts on human milk feeding.
- [underlined: What is the answer to the question]: There is not enough evidence to develop a summary statement for individual-behavioral interventions, programs, initiatives, and/or policies.

##### NIMHD framework: individual level – health care system domain

- [underlined: What evidence was found]: This section includes six articles. Most studies used technology as a key aspect of the intervention, including a smart-phone application, automated text messages, and internet-based education. None of the studies reported that the interventions impacted human milk feeding outcomes. There were several limitations across the studies, including small sample sizes, missing data, and how outcomes were measured.
- [underlined: What is the answer to the question]: Evidence suggests that individual-health care system interventions focused on technology may not impact human milk feeding outcomes in populations predominantly consisting of individuals from U.S. racial and ethnic minority groups. However, this evidence is limited by the small number of studies identified, relatively small sample sizes, marked heterogeneity in the interventions and populations assessed, and several risk of bias concerns.

##### NIMHD framework: community level – physical/built environment domain

- [underlined: What evidence was found]: This section includes 27 articles. The studies primarily looked at the impact of WIC programs and services or the impact of home visiting community health worker or peer mentor programs. The women included in these studies were primarily Hispanic, Black, or African American and of lower socioeconomic status. Most interventions or programs showed positive impacts on human milk feeding duration when compared to no intervention or program. Limitations in the evidence included missing data, how outcomes were measured, and not accounting for certain important factors.
- [underlined: What is the answer to the question]: Evidence suggests that community-physical/built environment interventions and programs, including home visiting programs delivered by community health workers or peer mentors, and certain WIC site programs and characteristics, may be associated with longer durations of any or exclusive human milk feeding among women who were predominantly Hispanic or Black/African American and of lower socioeconomic status. The evidence was limited by risk of bias concerns across all study designs.

##### NIMHD framework: community level – health care system domain

- [underlined: What evidence was found]: This section includes 48 articles. The studies primarily looked at the impact of Baby-Friendly hospital practices, group-based interventions, and a variety of individual-focused interventions delivered by providers such as nurses, doulas and lactation consultants. The women included in these studies were primarily Hispanic, Latina, Black, or African American, and of lower socioeconomic status. All studies on Baby-Friendly hospital practices reported at least some positive impacts on human milk feeding outcomes. Most group-based interventions also reported positive impacts on human milk feeding outcomes. The evidence for individual-focused interventions was less consistent. Limitations in the evidence included missing data, how outcomes were measured, and not accounting for certain important factors.
- [underlined: What is the answer to the question]: Evidence suggests that community-health care system interventions, programs, initiatives, and policies, including Baby-Friendly hospital practices and group-based programs, may be associated with more favorable human milk feeding outcomes in populations predominantly consisting of individuals from U.S. racial and ethnic minority groups. Among the interventions, programs, initiatives, and policies assessed, the evidence is most consistent for Baby-Friendly hospital practices. The evidence is predominantly generalizable to women who are Hispanic, Latina, or Black, or African American and, apart from studies that examined Baby-Friendly hospital practices, to women with a lower socioeconomic status. The evidence was limited by several risk of bias concerns across all study designs.

##### NIMHD framework: societal level – behavioral domain

- [underlined: What evidence was found]: This section includes 9 articles. The studies looked at changes made to the WIC food package in 2009, paid family leave laws, and laws that support human milk feeding. Several studies reported positive impacts on human milk feeding outcomes, but results were not consistent across the different policies assessed or by race ethnicity. Limitations in the evidence included missing data, how outcomes were measured, and not accounting for certain important factors.
- [underlined: What is the answer to the question]: Evidence suggests that societal-behavioral policies, including paid family leave laws and laws supporting human milk feeding, may be associated with more favorable human milk feeding outcomes in populations predominantly consisting of individuals from U.S. racial and ethnic minority groups. However, the policies and laws assessed across all the studies were heterogenous, the number of studies available for each category of policy or law was relatively small, and there was some inconsistency in results by racial and ethnic group. The evidence was further limited by several risk of bias concerns.

##### NIMHD framework: societal level – health care system domain

- [underlined: What evidence was found]: This section includes one article. The study found that Affordable Care Act-mandated lactation support services were associated with human milk feeding initiation.
- [underlined: What is the answer to the question]: There is not enough evidence to develop a summary statement for societal-health care system interventions, programs, initiatives, and policies.

## Abstract

#### Background

Racial and ethnic disparities in human milk feeding practices are present in the United States.^a^,^b^,^c^ It is of interest to identify interventions, programs, initiatives, and policies that may improve human milk feeding outcomes in diverse populations. To inform communication and program guidance on these topics, the Nutrition Evidence Systematic Review (NESR), housed in the Center for Nutrition Policy and Promotion (CNPP), Food and Nutrition Service (FNS), U.S. Department of Agriculture (USDA), conducted a rapid review project for the Office of Policy Support (OPS), FNS, USDA.

a Li R, Perrine CG, Anstey EH, Chen J, MacGowan CA, Elam-Evans LD. Breastfeeding trends by race/ethnicity among US children born from 2009 to 2015. JAMA Pediatr. 2019;173(12):e193319. doi:10.1001/jamapediatrics.2019.3319 31609438

b Chiang KV, Li R, Anstey EH, Perrine CG. Racial and ethnic disparities in breastfeeding initiation – United States, 2019. MMWR Morb Mortal Wkly Rep. 2021;70(21):769–774. doi:10.15585/mmwr.mm7021a1 34043611

c Jones KM, Power ML, Queenan JT, Schulkin J. Racial and ethnic disparities in breastfeeding. Breastfeed Med. 2015;10(4):186–196. doi:10.1089/bfm.2014.0152 25831234

One of the objectives of this project was to answer the following question: What interventions, programs, initiatives, and policies impact racial and/or ethnic disparities in human milk feeding in the United States, and do impacts vary across different racial and/or ethnic, socioeconomic, and geographic groups?

#### Methods

NESR analysts, in consultation with OPS, FNS, USDA, developed the rapid review protocol.

The study participants were parent-infant dyads, the interventions/exposures were interventions, programs, initiatives, and/or policies delivered during pregnancy and/or the postpartum period that address human milk feeding, the comparators were different interventions, programs, initiatives, and/or policies or no intervention, standard or care, and/or usual care, and the outcomes were measures of human milk feeding initiation, human milk feeding duration, exclusive human milk feeding duration, and meeting human milk feeding goals. Further, to be included, studies must have analyzed study participants by race and/or ethnicity or must have included participants that were predominantly from U.S. racial and/or ethnic minority groups.

Additional inclusion criteria were that studies must: a) use a primary study design (i.e., reviews and meta-analyses were excluded), b) be published in English in peer-reviewed journals, c) be conducted in the United States, and d) enroll participants with a range of health statuses (i.e., studies which only included infants admitted to a neonatal intensive care unit were excluded).

The NESR librarian conducted a literature search in PubMed (MEDLINE), Web of Science, and CINAHL to identify articles published between January 2009 and June 2022. Based on the pre-determined inclusion and exclusion criteria, one NESR analyst screened all electronic results, while a second NESR analyst independently dual-screened 30 percent of the electronic results at the title and abstract level and verified inclusion or exclusion for all electronic results at the full-text level.

A NESR analyst extracted data from each included article, and a second analyst verified accuracy of key components of the extraction. For all articles examining quantitative data, one NESR analyst independently conducted a formal risk of bias assessment, by study design, for each included article, then a second NESR analyst reviewed the assessments for accuracy. The NESR analysts qualitatively synthesized the evidence, with attention given to the overarching themes or key concepts from the findings, similarities and differences between studies, and factors that may have affected the results. The evidence was organized based on the National Institute on Minority Health and Health Disparities (NIMHD) Research Framework.^d^ The NIMHD research framework combines two dimensions to categorize and assess health determinants: levels of influence (individual, interpersonal, community, societal) and domains of influence (biological, behavioral, physical/built environment, sociocultural environment, health care system). The NESR analysts assessed the evidence based on its risk of bias, consistency, directness, precision, and generalizability and then developed summary statements.

d Alvidrez J, Castille D, Laude-Sharp M, Rosario A, Tabor D. The National Institute on Minority Health and Health Disparities research framework. Am J Public Health. 2019;109:S16–S20. doi:10.2105/AJPH.2018.304883 30699025

#### Results

Ninety-one articles met the inclusion criteria. The interventions, programs, initiatives, and policies examined in these articles were administered at six different combinations of NIMHD levels and domains of influence.

##### NIMHD framework: individual level – behavioral domain

- [underlined: Summary statement]: There is not enough evidence to develop a summary statement for individual-behavioral interventions, programs, initiatives, and policies.
- [underlined: Summary of the evidence]: One article met inclusion criteria and examined an individual-behavioral intervention, program, initiative, or policy. This randomized controlled trial (RCT) found that providing an ergonomic infant carrier had positive effects on breastfeeding rates at 6 months in Latina individuals living in a low-income community. However, due to only one study being identified at this level and domain, as well as limitations in this study’s precision and risk of bias, a summary statement was not developed.

##### NIMHD framework: individual level – health care system domain

- [underlined: Summary statement]: Evidence suggests that individual-health care system interventions focused on technology may not impact human milk feeding outcomes in racially and/or ethnically diverse populations. However, this evidence is limited by the small number of studies identified, relatively small sample sizes, marked heterogeneity in the interventions and populations assessed, and several risk of bias concerns.
- [underlined: Summary of the evidence]: Six articles (from four studies) met inclusion criteria and examined individual-health care system interventions, programs, initiatives, or policies. The evidence was primarily derived from RCTs; one article reported on a secondary, observational analysis of one of the included RCTs. Three of the RCTs utilized technology as a key aspect of the intervention (i.e., smart-phone application, automated text messages, internet-based education), while one RCT examined the impact of early placement of an etonogestrel contraceptive implant. None of the studies detected significant impacts on human milk feeding initiation, human milk feeding duration, and/or exclusive human milk feeding duration. However, the study which examined placement timing of an etonogestrel contraceptive implant was designed as a non-inferiority trial, and the lack of statistically significant effects between group was interpreted as a desirable outcome. Although the results of the three studies examining technological interventions were consistent, there were limitations in precision, risk of bias, and generalizability.

##### NIMHD framework: community level – physical/built environment domain

- [underlined: Summary statement]: Evidence suggests that community-physical/built environment interventions and programs, including home visiting programs delivered by community health workers or peer mentors, and certain WIC programs and services, may be associated with longer durations of any or exclusive human milk feeding among women who were predominantly Hispanic or Black/African American and of lower socioeconomic status. The evidence was limited by risk of bias concerns across all study designs.
- [underlined: Summary of the evidence]: Twenty-seven articles (from 24 studies) met inclusion criteria and examined community-physical/built environment interventions, programs, initiatives, or policies. Approximately half of the studies were RCTs, whereas the remaining studies were non-randomized controlled trials (NRCTs), prospective cohort studies (PCS), or cross-sectional studies. The studies were conducted predominantly or exclusively with women of lower socioeconomic status (SES). Study participants were most commonly Hispanic or Latina women and Black or African American women. Seventeen of the studies reported significant, favorable impacts on one or more human milk feeding outcomes; more consistent positive impacts were observed for exclusive human milk feeding duration, followed by human milk feeding duration, while impacts on human milk feeding initiation were predominantly null. Significant impacts were detected for a variety of interventions and programs, primarily when compared to exposure to no intervention or program. These interventions and programs included, broadly, Special Supplemental Nutrition Program for Women, Infants, and Children (WIC) programs and services (6 of 10 studies) and community health worker or peer mentor programs delivered at home or via the telephone (7 of 10 studies). The body of evidence was limited by several risk of bias concerns across all study designs.

##### NIMHD framework: community level – health care system domain

- [underlined: Summary statement]: Evidence suggests that community-health care system interventions, programs, initiatives, and policies, including Baby-Friendly hospital practices and group-based programs, may be associated with more favorable human milk feeding outcomes in populations predominantly consisting of individuals from U.S. racial and ethnic minority groups. Among the interventions, programs, initiatives, and policies assessed, the evidence is most consistent for Baby-Friendly hospital practices. The evidence is predominantly generalizable to women who are Hispanic, Latina, Black, or African American and, apart from studies that examined Baby-Friendly hospital practices, to women with a lower socioeconomic status. The evidence was limited by several risk of bias concerns across all study designs.
- [underlined: Summary of the evidence]: Forty-eight articles (from 47 studies) met inclusion criteria and examined community-health care system interventions, programs, initiatives, or policies. Approximately half of the studies were NRCTs or quasi-experimental, observational studies, whereas the remaining studies were RCTs, PCS, or cross-sectional studies. Most studies were conducted with women who were predominantly of lower SES. Study participants were most commonly Hispanic or Latina women and Black or African American women. Thirty-three of the studies detected significant, favorable impacts on one or more human milk feeding outcomes. These beneficial impacts were observed across a variety of interventions, programs, and policies, including: Baby-Friendly hospital practices (10 of 10 studies), group-based interventions (8 of 11 studies), and individual-focused interventions delivered by a variety of providers such as nurses, doulas, lactation consultants, and peer counselors (13 of 22 studies). Risk of bias concerns were noted across the body of evidence.

##### NIMHD framework: societal level – behavioral domain

- [underlined: Summary statement]: Evidence suggests that societal-behavioral policies, including paid family leave laws and laws supporting human milk feeding, may be associated with more favorable human milk feeding outcomes in populations predominantly consisting of individuals from U.S. racial and ethnic minority groups. However, the policies and laws assessed across all the studies were heterogenous, the number of studies available for each category of policy or law was relatively small, and there was some inconsistency in results by racial and/or ethnic group. The evidence was further limited by several risk of bias concerns.
- [underlined: Summary of the evidence]: Nine articles (from eight repeated cross-sectional studies) met inclusion criteria and examined societal-behavioral interventions, programs, initiatives, or policies. Four studies assessed the 2009 WIC food package revision, two studies assessed State paid family leave laws, and two studies assessed State laws pertaining to human milk feeding. Most studies reported one or more significant, favorable impact on human milk feeding outcomes. However, there were areas of inconsistency across the evidence, including: overall mixed results of the 2009 WIC food package revision, inconsistent results within racial/ethnic groups for studies examining paid family leave, and inconsistent benefits of State laws pertaining to human milk feeding by racial/ethnic group. Study sample sizes were generally large, and the study populations were generalizable to the populations of interest. However, there were several risk of bias concerns noted across the body of evidence.

##### NIMHD framework: societal level – health care system domain

- [underlined: Summary statement]: There is not enough evidence to develop a summary statement for societal-health care system interventions, programs, initiatives, and policies.
- [underlined: Summary of the evidence]: One article met inclusion criteria and examined a societal-health care system intervention, program, initiative, or policy. This quasi-experimental, repeated cross-sectional study assessed whether Affordable Care Act- (ACA-) mandated lactation support services were associated with breastfeeding initiation rates, finding that American Indian/Alaska Native, Black/African American, and White mothers had higher rates of breastfeeding initiation following the ACA mandate. However, due to only one study being identified at this level and domain, as well as limitations in this study’s risk of bias, a summary statement was not developed.

## Results

The methods used to answer Key Question 3, What interventions, programs, initiatives, and policies impact racial and/or ethnic disparities in human milk feeding in the United States, and do impacts vary across different racial and/or ethnic, socioeconomic, and geographic groups?, are described in Chapter 1. Table 5 describes the question specific analytic framework for Key Question 3 and Table 3 describes the inclusion and exclusion criteria for Key Question 3.

### Literature search and screening results

The literature search yielded 10,078 search results after the removal of duplicates (see Figure 10). Dual-screening resulted in the exclusion of 6,796 titles, 1,765 abstracts, and 1,283 full-texts articles. Reasons for full-text exclusion are in Appendix 5. The body of evidence included 234 articles across both Key Question 2 (see Chapter 3 for these results) and Key Question 3; Key Question 3 includes evidence from 91 articles.

Figure 10 Literature search and screen flowchart

Literature search and screen flowchart The literature search in PubMed, CINAHL, and Web of Science retrieved 10,078 records after removing duplicates. 6,796 titles, 1,765 abstracts, and 1,283 full-texts were excluded. 234 articles were included in the systematic review: 143 for key question 2 (71 quantitative articles, 72 qualitative articles) and 91 for key question 3.

### Overview of identified interventions, programs, initiatives, and policies

Ninety-one articles met the inclusion criteria for Key Question 3. The interventions, programs, initiatives, and policies examined in these articles were organized using the NIMHD research framework according to the level and domain at which the intervention, program, initiative, or policy was administered. Because of this organization scheme, interventions, programs, initiatives, or policies administered at one combination of NIMHD levels and domains may include components that are also present in the interventions, programs, initiatives, or policies administered at another combination of NIMHD levels and domains.

The interventions, programs, initiatives, and policies examined in these articles were administered at six different combinations of NIMHD levels and domains of influence; interventions, programs, initiatives, and policies administered at other intersections of the NIMHD research framework were not identified (illustrated in Figure 11).

Figure 11 Articles included in Key Question 3 organized by the NIMHD research framework with examples of included interventions, programs, initiatives, and policies^a^ a Parentheses indicate the number of articles for each category or type of intervention, program, initiative, or policy ^b^ b Abbreviations: ACA, Affordable Care Act; BF, breastfeeding; WIC, Special Supplemental Nutrition Program for Women, Infants, and Children

This figure illustrates the combination of NIMHD levels and domains of influence that the interventions, programs, initiatives, and policies identified in KQ3 were administered at. One article was identified for the individual level and behavioral domain: Ergonomic infant carrier (1 article). Six articles were identified for the individual level and health care system domain: Technology-focused interventions, e.g., educational smart phone application, automated text messages, web-based education (5 articles), Other (1 article). Twenty-seven articles were identified for the community level and physical/built environment domain: WIC programs and services (12 articles), Community health worker and peer educator/mentor home visiting programs (11 articles), Other (4 articles). Forty-eight articles were identified for the community level and health care system domain: Baby-Friendly hospital practices (11 articles), Group-based prenatal/postpartum interventions (11 articles), Individual breastfeeding education, counseling, support (22 articles), Other (3 articles). Nine articles were identified for the societal level and behavioral domain: WIC package revision (4 articles), Paid family leave laws (2 articles), State laws pertaining to breastfeeding (3 articles). One article was identified at the societal level and health care system domain: ACA-mandated lactation support (1 article). The included articles did not examine interventions, programs, initiatives, or policies at other combinations of NIMHD levels or domains.

| NIMHD Level
NIMHD Domain | Individual | Interpersonal | Community | Societal
Biological
Behavioral | [underlined: 1 article]; Ergonomic infant carrier (1) | | | [underlined: 9 articles]; WIC package revision (4); Paid family leave laws (2); State laws pertaining to BF (3)
Physical/Built environment | | | [underlined: 27 articles]; WIC programs and services (12); Community health worker and peer educator/mentor home visiting programs (11); Other (4)
Sociocultural environment
Health care system | [underlined: 6 articles]; Technology-focused interventions, e.g., educational smart phone application, automated text messages, web-based education (5); Other (1) | | [underlined: 48 articles]; Baby-Friendly hospital practices (11); Group-based prenatal/postpartum interventions (11); Individual BF education, counseling, support (22); Other (3) | [underlined: 1 article]; ACA-mandated lactation support (1)

### NIMHD framework: individual level – behavioral domain

#### Description of the evidence

This rapid review includes one article that was categorized as examining an individual-behavioral intervention, program, initiative, or policy.^144^ The characteristics and results of this study are presented in Table 15. This study was a randomized controlled trial (RCT) that assessed the effect of the provision of an ergonomic infant carrier on human milk feeding duration and exclusive human milk feeding duration. The study was conducted in a low-income community in California and the included participants were 95 percent Latina. The sample size was 79 participants.

#### Evidence synthesis

Only one study was identified that examined an individual-behavioral intervention, program, initiative, and/or policy, finding that provision of an ergonomic infant carrier had positive effects on breastfeeding at 6 months, but had no impact on breastfeeding rates at earlier time points or on exclusive breastfeeding rates at any time point assessed.^144^ The evidence was assessed using the following domains:

- [underlined: Consistency]: The evidence on individual-behavioral interventions, programs, initiatives, or policies consisted of a single study.
- [underlined: Precision]: The sample size of this study was relatively small and was likely underpowered based on post hoc power calculations; a priori power calculations were not conducted.
- [underlined: Risk of bias]: Although risk of bias due to randomization and deviations from intended interventions were assessed as low, risk of bias due to missing outcome data, measurement of the outcome, and selection of the reported results were assessed as having some concerns (Table 16).
- [underlined: Directness]: This study aligned with the population, intervention/exposure, comparator, and outcome in the analytic framework.
- [underlined: Generalizability]: Because this study was conducted with Latina individuals living in a low-income community, generalizability is limited to this subgroup.

#### Summary statement

There is not enough evidence to develop a summary statement for individual-behavioral interventions, programs, initiatives, and policies.

Table 15 Evidence for individual-behavioral interventions, programs, initiatives, and/or policies and human milk feeding outcomes (Key Question 3)^*^

Study | Study Participants | Intervention and Comparator; Adjustment for Race and/or Ethnicity | Significant Results | Non-Significant Results
Little, 2021 ^144^; RCT-Parallel; n = 41 (Int) and 38 (Comp) | Latina: 95%; SES: Low-income community; Location: CA | Int: Provision of ergonomic infant carrier; Comp: Waitlist control (6 mo); Analysis adjusted for race and/or ethnicity: No | HMF Duration; BF at 6 mo, Int vs Comp 68% vs 40%, p=0.02 | HMF Duration; BF at 6 wk and 3 mo; Exclusive HMF Duration; EBF at 6 wk, 3 mo, and 6 mo

* Abbreviations: %, percent; BF, breastfeeding; Comp, comparator; EBF, exclusive breastfeeding; HMF, human milk feeding; Int, intervention/exposure; mo, month; RCT, randomized controlled trial; SES, socioeconomic status; vs, versus; wk, week

Table 16 Risk of bias for randomized controlled trials examining individual-behavioral interventions, programs, initiatives, and/or policies and human milk feeding outcomes (Key Question 3)^*^

Article | Randomization | Deviations from intended interventions (effect of assignment) | Missing outcome data | Outcome measurement | Selection of the reported result
Little, 2021^144^ | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS

* Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2019 version)” ( Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ. 2019:366:l4898. doi: 10.1136/bmj.l4898 31462531 )

### NIMHD framework: individual level – health care system domain

#### Description of the evidence

This rapid review includes six articles (from four studies) that were categorized as examining individual-health care system interventions, programs, initiatives, or policies.^145–150^ The characteristics and results of each individual article are described in Table 17.

Most studies were RCTs^146–150^; one study was a secondary, observational analysis of one of the RCT^147,148^ and utilized a PCS design.^145^ Study sample sizes ranged from 18^150^ to 170^149^ total participants.

The studies were conducted in a variety of locations including St. Louis, MO,^145,147,148^ Salt Lake City, UT,^146^ Puerto Rico,^149^ and Hawaii.^149^ One study recruited a study sample from across the United States.^150^ Regarding SES, one study was conducted within the general population,^150^ one study did not provide data on SES,^146^ and the remaining two studies included individuals who had low-income or participated in WIC.^145,147–149^ There was racial and ethnic diversity across the included studies, with most studies including individuals from multiple racial and/or ethnic groups. Two studies predominantly included participants who were Black and/or African American^145,147,148,150^ whereas one article predominantly included participants who were Hispanic.^146^ The studies primarily described participants as women and/or mothers; this terminology is used throughout this section, as appropriate.

Most of the individual-health care system interventions aimed to impact human milk feeding outcomes through technology, including a smart-phone application,^145,147,148^ automated text messages,^149^ and web-based education.^150^ One study examined the impact of timing of an etonogestrel contraceptive implant on human milk feeding outcomes.^146^ Two of the interventions were delivered during the postpartum period,^146,149^ while the remaining two interventions were delivered across both the prenatal and postpartum period.^145,147,148,150^

Five articles reported on human milk feeding initiation,^145–148,150^ all six articles reported on human milk feeding duration, and five articles reported on exclusive human milk feeding duration.^145–148,150^ None of the studies reported on meeting human milk feeding goals.

#### Evidence synthesis

Four studies examined individual-health care system interventions, programs, initiatives, or policies, none of which detected significant impacts on human milk feeding initiation, human milk feeding duration, and/or exclusive human milk feeding duration.^145–150^ However, one study on the timing of etonogestrel contraceptive implant placement was designed as a noninferiority trial; therefore, the lack of statistically significant effects was interpreted as a desirable outcome.^146^ Although three of the four studies assessed utilized technology as a key aspect of the intervention, there was variability in the type of technology used (i.e., smart-phone application, automated text messages, internet-based education).^145,147–150^ The evidence was assessed using the following domains:

- [underlined: Consistency]: None of the studies reported significant impacts of the varied interventions assessed on human milk feeding outcomes. However, the study that examined the timing of etonogestrel contraceptive implant was designed as a noninferiority trial.^146^
- [underlined: Precision]: The studies were generally small. Several of the analyses were underpowered or were not powered specifically for the human milk feeding outcomes of interest.
- [underlined: Risk of bias]: Several risk of bias domains were of concern across the studies (see Table 18 and Table 19). Among the RCT, all studies were assessed as having some concerns due to missing outcome data and outcome measurement, while most studies were assessed as having some concerns or high risk of bias due to selection of reported result. The one article that reported observational, secondary analyses of one of the RCT was assessed as having serious risk of bias due to confounding and moderate risk of bias due to missing data, outcome measurement, and selection of reported result.
- [underlined: Directness]: Most studies aligned with the population, intervention/exposure, comparator, and outcome in the analytic framework. Exceptions were the study on the timing of etonogestrel contraceptive implant placement, which assessed whether early placement resulted in similar human milk feeding outcomes,^146^ and a secondary analysis of the study on the educational smart-phone app which analyzed data by quartile of app usage.^145^
- [underlined: Generalizability]: The generalizability of these studies, taken as a whole, is difficult to assess due to the relatively distinct interventions that were assessed and populations that were included. Specifically, the etonogestrel contraceptive implant study was conducted in a predominantly Hispanic population with no information on SES,^146^ the web-based human milk education intervention was assessed in an exclusively African American/Black population who were intending to breastfeed and had mild to moderate depressive symptoms,^150^ the automated texting intervention was assessed among individuals who participated in WIC and were predominantly Hispanic,^149^ and the educational smart-phone application intervention was assessed among nulliparous women who had low-income and were predominantly Black.^145,147,148^

#### Summary statement

Evidence suggests that individual-health care system interventions focused on technology may not impact human milk feeding outcomes in populations predominantly consisting of individuals from U.S. racial and ethnic minority groups. However, this evidence is limited by the small number of studies identified, relatively small sample sizes, marked heterogeneity in the interventions and populations assessed, and several risk of bias concerns.

Table 17 Evidence for individual-health care system interventions, programs, initiatives, and/or policies and human milk feeding outcomes (Key Question 3)^*^,^†^

Study | Study Participants | Intervention and Comparator; Adjustment for Race and/or Ethnicity | Significant Results | Non-Significant Results
Griffin, 2021 ^145^; PCS; n = 30-44 (Int) and 34-41 (Comp) | Asian: 0%; Black: 85%; Hispanic: 3%; Other: 5%; White: 7%; 100% nulliparous; SES: Low-income (all with Medicaid or no health insurance); Location: St. Louis, MO | Int: Highest quartile of usage of smart-phone app with educational content related to BF; Comp: Lowest quartile of usage of smart-phone app with educational content related to BF; Analysis adjusted for race and/or ethnicity: No | | HMF Initiation; BF Initiation; HMF Duration; Sustained BF at 2 d, 6 wk, 3 mo, and 6 mo; Exclusive HMF Duration; EBF at 2 d, 6 wk, 3 mo, and 6 mo
Gurtcheff, 2011 ^146^; RCT-Parallel; n = 28-34 (Int) and 29-35 (Comp) | Other: ~9%; White: ~24%; White, Hispanic: ~67%; SES: NR; Location: Salt Lake City, UT | Int: Early insertion of etonogestrel contraceptive implant (1-3 d postpartum); Comp: Standard insertion of etonogestrel contraceptive implant (4-8 wk postpartum); Analysis adjusted for race and/or ethnicity: No | | HMF Initiation; Any BF at Hospital Discharge, Full BF at Hospital Discharge; HMF Duration; Any BF at 2 wk, 4-8 wk, 3 mo, and 6 mo; Exclusive HMF Duration; Full BF at 2 wk, 4-8 wk, 3 mo, and 6 mo
Lewkowitz, 2020 ^147^; RCT-Parallel; n = 60-84 (Int) and 67-85 (Comp) | Asian: ~1%; Black: ~82%; Hispanic: ~2%; Other: ~4%; White: ~11%; 100% nulliparous; SES: Low-income (all with Medicaid or no health insurance); Location: St. Louis, MO | Int: Smart-phone app (Breastfeeding Friend) with on-demand education and videos on breastfeeding and neonatal support, beginning at 36 wk pregnant; Comp: Control smartphone application with digital breastfeeding handouts; Analysis adjusted for race and/or ethnicity: No | | HMF Initiation; BF Initiation; HMF Duration; Sustained BF at 2 d, 6 wk, 3 mo, and 6 mo; Exclusive HMF Duration; EBF at 2 d, 6 wk, 3 mo, and 6 mo
Lewkowitz, 2021 ^148^; RCT-Parallel; n = 29-41 (Int) and 39-46 (Comp) | Asian: ~2%; Black: ~75%; Hispanic: ~2%; Other: ~4%; White: ~17%; 100% nulliparous and planned to EBF; SES: Low-income (all with Medicaid or no health insurance); Location: St. Louis, MO | Int: Smart-phone app (Breastfeeding Friend) with on-demand education and videos on breastfeeding and neonatal support, beginning at 36 wk pregnant; Comp: Control smartphone application with digital breastfeeding handouts; Analysis adjusted for race and/or ethnicity: No | | HMF Initiation; BF Initiation; HMF Duration; Sustained BF at 2 d, 6 wk, 3 mo, and 6 mo; Exclusive HMF Duration; EBF at 2 d, 6 wk, 3 mo, and 6 mo
Palacios, 2018 ^149^; RCT-Parallel; n = 84 (Int) and 86 (Comp) | American Indian: 5%; Asian: 21%; Black: 14%; Hispanic: 61%; Pacific Islander: 9%; White: 25%; SES: WIC participants; Location: PR and HI | Int: 18 short message service (weekly for 4 mo) based on transtheoretical model on infant feeding practices delivered during the postpartum period; Comp: 18 short message service (weekly for 4 mo) on general infant health delivered during the postpartum period; Analysis adjusted for race and/or ethnicity: No | | HMF Duration; BF (partial/EBF) at 4 mo
Pezley, 2022 ^150^; RCT-Parallel; n = 10-11 (Int) and 7 (Comp) | African American/Black: 100%; Hispanic: 4%; 100% intending to BF with mild to moderate depressive symptoms; SES: General population; Location: United States | Int: Web-based CBT intervention (6 wk during pregnancy and 6 wk postpartum) to manage mood, lower risk of postpartum depression plus HM feeding education and support including at least two lactation support calls and weekly text messages postpartum.; Comp: Web-based CBT intervention to manage mood, lower risk of postpartum depression alone; Analysis adjusted for race and/or ethnicity: No | | HMF Initiation; HMF Initiation; HMF Duration; Any HMF at 6 wk, 12 wk; Exclusive HMF Duration; Exclusive HMF at 6 wk, 12 wk

* %: percent; ~: approximately; BF: breastfeeding; CBT: cognitive behavioral therapy; Comp: comparator; d: day; EBF: exclusive breastfeeding; HMF: human milk feeding; Int: intervention/exposure; mo: month; NR: not reported; RCT: randomized controlled trial; SES: socioeconomic status; vs: versus; wk: week

† Griffin et al 2021, Lewkowitz et al 2020, and Lewkowitz et al 2021 are from one study

Table 18 Risk of bias for randomized controlled trials examining individual-health care system interventions, programs, initiatives, and/or policies and human milk feeding outcomes (Key Question 3)^*^

Article | Randomization | Deviations from intended interventions (effect of assignment) | Deviations from intended interventions (per-protocol) | Missing outcome data | Outcome measurement | Selection of the reported result
Gurtcheff, 2011^146^ | LOW | - | HIGH | SOME CONCERNS | SOME CONCERNS | HIGH
Lewkowitz, 2020^147^ | LOW | LOW | - | SOME CONCERNS | SOME CONCERNS | LOW
Lewkowitz, 2021^148^ | LOW | LOW | - | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS
Palacios, 2018^149^ | SOME CONCERNS | LOW | - | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS
Pezley, 2022^150^ | LOW | LOW | - | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS

* Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2019 version)” ( Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ. 2019:366:l4898. doi: 10.1136/bmj.l4898 31462531 )

Table 19 Risk of bias for observational studies examining individual-health care system interventions, programs, initiatives, and/or policies and human milk feeding outcomes (Key Question 3)^*^

Article | Confounding | Selection of participants | Classification of exposures | Deviations from intended exposures | Missing data | Outcome measurement | Selection of the reported result
Griffin, 2021^145^ | SERIOUS | LOW | LOW | LOW | MODERATE | MODERATE | MODERATE

* Possible ratings of low, moderate, serious, critical, or no information determined using the “Risk of Bias for Nutrition Observational Studies” tool (RoB-NObs) ( Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.)

### NIMHD framework: community level – physical/built environment domain

#### Description of the evidence

This rapid review includes 27 articles (from 24 studies) that examined community-physical/built environment interventions, programs, initiatives, or policies.^151–177^ The characteristics and results of each individual article are described in Table 20.

A variety of study designs were used across the body of evidence, including 12 parallel-RCT,^153,159,162,165,166,168,170,171,173–175,177^ 1 cluster-RCT,^176^ 5 NRCTs,^154,155,157,158,160,164^ 5 PCS^151,156,161,167,172^ (2 of which were secondary analyses of RCTs), 2 cross-sectional or repeated cross-sectional studies,^152,163^ and 1 article that included analyses based on a parallel-RCT and NRCT design.^169^ Data sources included across the articles were predominantly unnamed, but included the National Health and Nutrition Examination Survey (NHANES),^163^ the WIC Infant and Toddler Feeding Practices Study 2 (ITFPS-2),^156^ the Texas Department of State Health Services WIC Infant Feeding Practices Survey (IFPS),^152^ the Delta Healthy Sprouts Project,^175^ the Early Childhood Obesity Prevention Program,^153^ the Lactation Advice thru Texting Can Help (LATCH) pilot^159^ and study,^167,168^ and the LIFE-Moms Consortium (Missouri site).^162^ Sample sizes ranged from 36^177^ to 33,582^158^ total participants.

The studies were conducted in a variety of locations across the United States, including the Midwest,^151,155,162,169^ the Northeast,^153,154,157–159,161,167,168,174,177^ the Southeast,^165,166,175^ the Southwest,^152,161,164,171^ the West Coast,^160,170,172,173,176^ and nationally.^156,163^ Only one study noted being conducted exclusively in rural areas.^175^ In regard to SES, all studies were conducted among individuals predominantly of lower SES, including many studies among individuals who were WIC-eligible or participated in WIC,^152,154,156–159,163,164,167,168,170,171,176,177^ with the exception of one study that included individuals from two sites – one with a high proportion of WIC participants and one with a low proportion of WIC participants.^161^ Many studies predominantly or exclusively enrolled Hispanic and/or Latina participants,^159,160,164–168,171,174,176,177^ while a few studies predominantly or exclusively enrolled African American and/or Black individuals.^155,162,175^ The remaining studies enrolled individuals across several racial and ethnic groups more broadly, however, Hispanic, Latina, Black, and African American individuals were still more commonly or prominently represented than individuals of other racial and/or ethnic groups.^151–154,156–158,161,163,169,170,172,173^ The studies primarily described participants as women or mothers; this terminology is used throughout this section, as appropriate.

The studies examined a variety of community-physical/built environment, initiatives, and policies. Twelve articles (from 10 studies) examined the impact of WIC participation or the impact of WIC programs and services, such as peer counseling and access to lactation consultants.^152,154,156–159,163,164,167,168,170,176^ Several of these studies examined the impact of enhancing existing WIC programs, including adding a texting component to a peer counseling program^159,167,168^ and adding peer counseling for fathers to a peer counseling program for mothers.^164^ Eleven articles (from 10 studies, primarily RCT) assessed the impact of community health worker or peer educator/mentor programs, delivered in the participants’ homes^153,162,165,166,169,171–175^ or via the telephone.^160^ A few of these studies compared existing programs to versions which were enhanced with content on human milk feeding.^153,162,175^ The remaining studies examined a diverse group of interventions and exposures including programmatic elements of a public health program,^151^ a community-based group intervention,^155^ informal breastfeeding support group with professional lactation care,^161^ and financial incentives.^177^ Most studies assessed interventions and programs implemented during both the prenatal and postnatal periods,^151,152,154–159,164–175^ although a few studies examined interventions or programs delivered during either the prenatal period^152,162^ or the postnatal period.^152,153,160,161,163,176,177^

Thirteen articles assessed human milk feeding initiation,^152,153,155,157,158,162,163,165,166,169,170,174,175^ 18 articles assessed human milk feeding duration,^151,153,156,158,160,161,163–166,168–173,176,177^ 10 articles assessed exclusive human milk feeding duration,^154,156,159,160,166–168,170,174,176^ and 2 articles assessed the outcome of meeting human milk feeding goals.^159,161^

#### Evidence synthesis

Twenty-four studies (approximately half from RCT) examined community-physical/built environment interventions, programs, initiatives, or policies,^151–177^ 17 of which detected significant, favorable impacts on human milk feeding initiation, human milk feeding duration, and/or exclusive human milk feeding duration.^151–158,160,161,165–170,172–174,177^ More specifically, 4 of 12 studies reported significant, favorable impacts on human milk feeding initiation,^152,153,155,157,158,162,163,165,166,169,170,174,175^ 9 of 17 studies reported significant, favorable impacts on human milk feeding duration,^151,153,156,158,160,161,163–166,168–173,176,177^ and 7 of 9 studies reported significant, favorable impacts on exclusive human milk feeding duration.^154,156,159,160,166–168,170,174,176^ Only two studies assessed whether individuals met their personal human milk feeding goals, with neither reporting significant impacts of the tested intervention or program on this outcome.^159,161^

Significant impacts were detected across a variety of interventions and programs. Among studies examining WIC programs and services, 6 of 10 reported positive impacts on 1 or more human milk feeding outcomes.^152,154,156–159,163,164,167,168,170,176^ The specific outcomes impacted across the studies varied, with two of four studies reporting positive impacts on human milk feeding initiation,^152,157,158,163,170^ three of seven studies reporting positive impacts on human milk feeding duration,^156,158,163,164,168,170,176^ and four of six studies reporting positive impacts on exclusive human milk feeding duration.^154,156,159,167,168,170,176^ Among studies examining community health worker or peer mentor programs delivered at home or via telephone, 7 of 10 reported positive impacts on 1 or more human milk feeding outcomes.^153,160,162,165,166,169,171–175^ The specific outcomes impacted across the studies varied, with four out of seven studies reporting positive impacts on human milk feeding duration^153,160,165,166,169,171–173^ and three of three studies reporting positive impacts on exclusive human milk feeding duration,^160,166,174^ while only one of seven studies reported positive impacts on human milk feeding initiation.^153,162,165,166,169,174,175^ For both these categories of interventions and programs, significant, positive impacts were predominantly observed when compared to no program^152,154,156–158,160,165,166,169–174,176^ (versus studies that aimed to enhance existing programs).^153,159,162,164,167,168,175^ The remaining interventions or programs examined were diverse, limiting comparison between studies.^151,155,161,177^

The evidence was assessed using the following domains:

- [underlined: Consistency]: A majority of the studies reported positive effects or impacts on one or more human milk feeding outcomes. However, more consistent positive impacts were observed for exclusive human milk feeding duration, followed by human milk feeding duration; impacts on human milk feeding initiation were predominantly null. Although the interventions, programs, initiatives and policies assessed were diverse, which somewhat limits the ability to assess consistency, positive associations with human milk feeding outcomes tended to be reported for community health worker and peer mentor led programs (primarily delivered at home) and WIC programs and services promoting breastfeeding, when either were compared to no exposure to these programs or services.
- [underlined: Precision]: Sample size varied across the studies, ranging from small (<50 participants) to large (>1,000 participants). Although significant effects were detected across studies of varying size, smaller studies were more likely to report null results.
- [underlined: Risk of bias]: Several risk of bias domains were of concern across studies and interventions/exposures (see Table 21, Table 22, Table 23, Table 24). For RCT, NRCT, and observational studies, risk of bias due to missing data or missing outcome data, risk of bias due to outcome measurement, and risk of bias due to selection of reported results were predominantly assessed as having some concerns or moderate. For NRCT and observational studies, risk of bias due to confounding was most commonly assessed as serious. Finally, among RCT that assessed home visiting programs delivered by parent educators or community health workers, there were some concerns regarding randomization due to a lack of information on the randomization method and/or allocation sequence concealment.
- [underlined: Directness]: The studies generally aligned with the population, intervention/exposure, comparator, and outcome in the analytic framework. However, two studies, one on a WIC peer counseling texting program^167^ and one on a parent educator home visiting program,^172^ were secondary analyses of trials and less direct in regards to the intervention. A third, less direct study examined a responsive bottle-feeding intervention in WIC clinics to reduce rapid infant weight gain; in contrast to other studies, a lack of significant impact on any or exclusive breastfeeding in this study was interpreted as a positive outcome.^176^
- [underlined: Generalizability]: Almost all studies were conducted with women who participated in WIC or who were predominantly or exclusively low-income, limiting generalizability of the evidence to women of lower SES. A large proportion of the studies included participants who were predominantly Hispanic and/or Latina, and a few studies included predominantly Black and/or African American participants. Many of the studies included women from multiple racial and/or ethnic groups, but across these studies Hispanic, Latina, Black, and/or African American women were still the most represented racial and/or ethnic groups. Women from other racial and/or ethnic groups were less represented. Only one study explicitly noted that it was conducted in a rural area; all other studies were conducted in cities, greater metropolitan areas, statewide, or nationwide, or did not provide detailed information on the study location.

#### Summary statement

Evidence suggests that community-physical/built environment interventions and programs, including home visiting programs delivered by community health workers or peer mentors, and certain WIC programs and services, may be associated with longer durations of any or exclusive human milk feeding among women who were predominantly Hispanic or Black/African American and of lower socioeconomic status. The evidence was limited by risk of bias concerns across all study designs.

Table 20 Evidence for community-physical/built environment interventions, programs, initiatives, and/or policies and human milk feeding outcomes (Key Question 3)^*^,^†^

Study | Study Participants | Intervention and Comparator; Adjustment for Race and/or Ethnicity | Significant Results | Non-Significant Results
Caine, 2012 ^151^; PCS; n = 395 | Black (Non-Hispanic): 63%; Hispanic: 14%; Other: 1%; White (Non-Hispanic): 22%; SES: Predominantly low-income; Location: Indianapolis, IN | Int: Exposure to certain programmatic elements of Indianapolis Healthy Start program prenatally and/or postnatally (among Indianapolis Healthy Start participants); Comp: No exposure to certain programmatic elements of Indianapolis Healthy Start program prenatally and/or postnatally (among Indianapolis Healthy Start participants); Analysis adjusted for race and/or ethnicity: Yes | HMF Duration; BF continuation to at least 6 mo, OR (95% CI) High vs Low (ref) intensity of case management services: 3.55 (1.69, 7.45) | HMF Duration; BF continuation to at least 6 mo: Moderate vs Low intensity of case management services, Referral to lactation consultant vs Not
Campbell, 2014 ^152^; TX Department of State Health Services WIC IFPS 2009; CS; n = 3,070 | Asian: 1%; Black: 13%; Hispanic: 64%; Native American: <1%; Other: <1%; White: 20%; 100% without previous BF experience; SES: WIC participants; Location: TX | Int: WIC peer-counselor contact during pregnancy, in hospital, and/or after delivery; Comp: No WIC peer-counselor contact; Analysis adjusted for race and/or ethnicity: No | HMF Initiation; BF Initiation, OR (95% CI); During pregnancy vs Not (ref): 1.36 (1.12, 1.66), p=0.0024; In hospital vs Not (ref): 2.06 (1.54, 2.75), p<0.0001; After delivery vs Not (ref): 1.85 (1.53, 2.24), p<0.0001; During pregnancy and in hospital vs Not (ref): 2.07 (1.51, 2.84); During pregnancy and after delivery vs Not (ref): 1.56 (1.30, 1.88); In hospital and after delivery vs Not (ref): 2.07 (1.51, 2.83); During pregnancy, in hospital, and after delivery vs Not (ref): 2.00 (1.44, 2.76)
Cloutier, 2018 ^153^; Early Childhood Obesity Prevention Program; RCT-Parallel; n = 18-24 (Int) and 12-17 (Comp) | African American/Black: 19%; Hispanic: 60%; Other: 19%; Unknown: 2%; SES: Predominantly low-income; Location: Hartford, CT | Int: Postnatal home visitation program (Nurturing Families Network+) which includes education on child development, parenting, family well-being with enhanced support on BF, goal-setting, self-monitoring, behavioral strategies, toolkit to support changes, and linkages to community programs that support behavior change delivered weekly for 2 mo then biweekly by trained parents as teachers during the postpartum period; Comp: Postnatal home visitation program (Nurturing Families Network) which includes education on child development, parenting, family well-being, delivered weekly for 2 mo then biweekly by trained parents as teachers during the postpartum period; Analysis adjusted for race and/or ethnicity: No | HMF Duration; BF at 6 mo, Int vs Comp 50% vs 8%, p=0.03; BF at 12 mo, Int vs Comp 44% vs 0%, p=0.003 | HMF Initiation; BF initiation; HMF Duration; Age when BF stopped
Edmunds, 2017 ^178^; NRCT; n = 362 (Int), 688 (Comp - Baseline), and 408 (Comp - Contemporaneous) | Hispanic: 51%; Non-Hispanic Black: 31%; Non-Hispanic Other: 7%; Non-Hispanic White: 11%; SES: WIC participants; Location: NY | Int: WIC initiative (You Can Do It) with screening (using 26-item Breastfeeding Attrition Prediction Tool) administered during the first trimester and tailored counseling with WIC educators throughout pregnancy and the early postpartum period; Comp: Usual care (Baseline cohort and Contemporaneous cohort); Analysis adjusted for race and/or ethnicity: Yes | Exclusive HMF Duration; EBF, Int vs Comp - Baseline (ref), OR (95% CI); At 7 d: 1.6 (1.2, 2.3), p<0.05; At 30 d: 1.9 (1.3, 2.8), p<0.05; At 60 d: 1.8 (1.2, 2.7), p<0.05; EBF, Int vs Comp - Contemporaneous (ref), OR (95% CI); At 7 d: 1.6 (1.1, 2.5), p<0.05; At 30 d: 1.6 (1.0, 2.5), p<0.05; EBF by race and/or ethnicity, Int vs Comp - Baseline and Contemporaneous; Black; At 30 d: Int > Comps, Data NR, p=0.01; At 60 d: Int > Comps, Data NR, p=0.02; Hispanic; At 30 d: Int > Comps, Data NR, p=0.04; At 60 d: Int > Comps, Data NR, p=0.002 | Exclusive HMF Duration; EBF at 60 d (Int vs Comp - Contemporaneous); EBF at 7 d, 30 d, 60 d: White; EBF at 7 d: Black and Hispanic
Gabbe, 2017 ^155^; NRCT; n = 67 (Int), 442 (Comp – Years 2007-2010), and 339 (Comp – Years 2011-2014) | African American/Non-Hispanic Black: 72%; SES: Predominantly low-income; Location: Columbus, OH | Int: Community-based, weekly intervention (Moms2B) in a group setting for pregnant women with education focused on nutrition, pregnancy, and infant safety topics. Sessions lasted 2 h, social support and relationship building was prioritized, and a meal was provided. Attendance was not prescribed and ranged from 1-26 sessions. Staff visited mother in hospital after delivery to promote BF. Nurse home visits occur, and community center visits continue after birth.; Comp: Women living in the same location with Medicaid-covered births in the 3 y before (2007-2010) and 4 y after (2011-2014) Moms2B began; Analysis adjusted for race and/or ethnicity: No | HMF Initiation; BF at hospital discharge, Int vs Comp (2011-2014) vs Comp (2007-2010); 75.5% vs 71.4% vs 37.9%, p<0.001
Gleason, 2020 ^156^; WIC ITFPS-2; PCS; n = 1,235 | Hispanic: 52%; Non-Hispanic Black: 17%; Non-Hispanic Other: 7%; Non-Hispanic White: 24%; SES: WIC participants; Location: U.S. national sample | Int: WIC site-level characteristics related to staffing, policies, and practices that support BF; Comp: No WIC site characteristic; Analysis adjusted for race and/or ethnicity: Yes | HMF Duration; Any BF, OR (95% CI); Breastfeeding peer counselor program vs None (ref); At 2 mo: 1.26 (1.18, 1.35), p<0.001; At 6 mo: 0.89 (0.83, 0.95), p<0.001; At 12 mo: 0.63 (0.59, 0.68), p<0.001; Access to IBCLC vs None (ref); At 2 mo: 0.90 (0.83, 0.97), p=0.005; At 6 mo: 1.09 (1.01, 1.18), p=0.02; At 12 mo: 1.45 (1.33, 1.58), p<0.001; Was NOT permitted formula issuance for BF infants during first 30 d vs Was (ref); At 2 mo: 1.23 (1.16, 1.31), p<0.001; At 6 mo: 1.39 (1.31, 1.48), p<0.001; Provision of home visits vs None (ref); At 6 mo: 1.41 (1.32, 1.51), p<0.001; At 12 mo: 1.54 (1.43, 1.66), p<0.001; Any staff member can provide breast pump education vs Not (ref); At 6 mo: 1.11 (1.04, 1.18), p<0.001; At 12 mo: 0.85 (0.79, 0.91), p<0.001; Total Site Characteristic Score (continuous); At 2 mo: 1.09 (1.06, 1.12), p<0.001; At 6 mo: 1.19 (1.16, 1.23), p<0.001; At 12 mo: 1.08 (1.04, 1.11), p<0.001; Total Site Characteristic Score, 3-5 vs 1-2 (ref); At 6 mo: 1.28 (1.21, 1.36), p<0.001; Exclusive HMF Duration; Fully BF, OR (95% CI); Breastfeeding peer counselor program vs None (ref); At 6 mo: 0.77 (0.71, 0.83), p<0.001; At 12 mo: 0.76 (0.69, 0.84), p<0.001; Access to IBCLC vs None (ref); At 2 mo: 1.37 (1.25, 1.50), p<0.001; At 6 mo: 1.68 (1.54, 1.83), p<0.001; At 12 mo: 2.18 (1.97, 2.42), p<0.001; Was NOT permitted formula issuance for BF infants during first 30 d vs Was (ref); At 2 mo: 1.12 (1.04, 1.21), p=0.002; Provision of home visits vs None (ref); At 2 mo: 1.52 (1.41, 1.65), p<0.001; At 6 mo: 2.13 (1.98, 2.30), p<0.001; At 12 mo: 2.00 (1.83, 2.20), p<0.001 Any staff member can provide breast pump education vs Not (ref); At 2 mo: 1.35 (1.26, 1.45), p<0.001; At 6 mo: 1.37 (1.27, 1.47), p<0.001; At 12 mo: 1.24 (1.13, 1.36), p<0.001; Total Site Characteristic Score (continuous); At 2 mo: 1.26 (1.21, 1.31), p<0.001; At 6 mo: 1.36 (1.31, 1.42), p<0.001; At 12 mo: 1.40 (1.34, 1.47), p<0.001; Total Site Characteristic Score, 3-5 vs 1-2 (ref); At 2 mo: 1.59 (1.48, 1.70), p<0.001; At 6 mo: 2.09 (1.95, 2.23), p<0.001; At 12 mo: 2.11 (1.94, 2.29), p<0.001 | HMF Duration; Any BF at 2 mo: Provision of home visits; Any staff member can provide breast pump education; Total Site Characteristic Score (3-5 vs 1-2); Any BF at 12 mo: Was NOT permitted formula issuance for BF infants during first 30 d; Total Site Characteristic Score (3-5 vs 1-2); Exclusive HMF Duration; Fully BF at 2 mo: Breastfeeding peer counselor program Fully BF at 6 mo and 12 mo: Was NOT permitted formula issuance for BF infants during first 30 d
Gross, 2009 ^157^; NRCT; n = 8,747 (Int), 4,527 (Int 2), 5,515 (Comp) | Hispanic: 24%; Non-Hispanic African American: 51%; Non-Hispanic Other: 3%; Non-Hispanic White: 22%; Unknown Race: <1%; SES: WIC participants; Location: MD | Int: WIC peer-counseling BF support (5-15 min phone calls or in-person visits at WIC appt); Int 2: Usual care with access to IBCLC resource; Comp: Usual care; Analysis adjusted for race and/or ethnicity: Yes | HMF Initiation; BF Initiation, OR (95% CI); All; Int vs Comp (ref): 1.27 (1.18, 1.37), p<0.01; Int vs Int 2 (ref): 1.22 (1.13, 1.32); Interaction with Race and/or Ethnicity - All with Comp/Non-Hispanic African American (ref); Int/Non-Hispanic African American: 1.47 (1.33, 1.61); Int 2/Non-Hispanic African American: 1.16 (1.04, 1.30); Int/Non-Hispanic White: 1.17 (1.05, 1.30); Int 2/Non-Hispanic White: 1.47 (1.33, 1.61); Comp/Other: 1.67 (1.13, 2.46); Int/Other: 2.80 (2.22, 3.55); Int 2/Other: 2.48 (1.64, 3.74); Comp/Hispanic: 4.09 (3.36, 4.94); Int/Hispanic: 4.82 (4.27, 5.45); Int 2/Hispanic: 3.24 (2.75, 3.80) | HMF Initiation; BF Initiation: Int2 vs Comp (All); Comp/Non-Hispanic White vs Comp/Non-Hispanic African American
Gross, 2011 ^158^; NRCT; n = 9,668-15,891 (Int), 4,280-7,863 (Int 2), and 4,771-10,028 (Comp) | Hispanic: 24%; Non-Hispanic African; American: 51%; Non-Hispanic Other: 3%; Non-Hispanic White: 22%; SES: WIC participants; Location: MD | Int: WIC peer-counseling BF support prenatally and postnatally; Int 2: Usual care with access to IBCLC resource prenatally and postnatally; Comp: Usual care; Analysis adjusted for race and/or ethnicity: No (however, article notes that adjustment for race and/or ethnicity did not change statistical significance) | HMF Initiation; BF Initiation; Overall: p=0.000; Int vs Comp (ref): 61.6% vs 47.6%, p<0.001; Int vs Int2 (ref): 61.6% vs 54.4%, p<0.001; HMF Duration; BF Duration, Mean (SD); Overall: p=0.000; Int vs Int2 (ref): 38.67 (47.78) vs 42.30 (50.82) d, p=NR; Int2 vs Comp (ref): 42.30 (50.82) d vs 38.18 (49.83) d, p=NR
Harari, 2018 ^159^; Lactation Advice thru Texting Can Help (LATCH) Pilot; RCT-Parallel; n = 30 (Int) and 22 (Comp) | Black: 17%; Hispanic: 75%; Other: 2%; White: 6%; SES: WIC participants; Location: CT | Int: Peer counseling support program with web-based texting BF support including automated texts and texts with WIC peer counselor prenatally and postnatally; Comp: Peer counseling support program prenatally and postnatally; Analysis adjusted for race and/or ethnicity: No | | Exclusive HMF Duration; EBF at 2 wk Postpartum; Meeting HMF Goals; Met BF Goals
Harris-Luna, 2018 ^160^; NRCT; n = 31 (Int) and 30 (Comp) | Hispanic: 100%; SES: Predominantly low-income; Location: Southern CA | Int: Telephone BF support provided by certified and trained promotoras (weekly calls for first 4 wk postpartum, then biweekly for up to 12 wk postpartum); Comp: Usual care; Analysis adjusted for race and/or ethnicity: No | HMF Duration; BF Duration at 12 wk, Int vs Comp, Mean (SD); 62.24 (10.22) d vs 48.45 (9.45) d, p<0.01; Exclusive HMF Duration; EBF at 12 wk, Int vs Comp (ref), OR (95% CI); 3.39 (1.01, 11.46), p=0.04
Jenkins, 2020 ^161^; PCS; n = 150-409 | Asian: <1% (TX), 6% (MA); Black American: 6% (TX), 3% (MA); Black Other: <1% (TX), 0% (MA); Caucasian: 9% (TX), 83% (MA); Hispanic: 82% (TX), 5% (MA); Indian: 0% (TX), 3% (MA); Other: 1% (TX), 0% (MA); SES: WIC participants - MA: 3%, TX: 99%; Location: MA (30min outside Boston) & San Antonio, TX | Int: Attendance at a Baby Café ≥5 times postnatally; Baby Cafés offer peer support, lactation consultants, weekly sessions, BF-positive messaging, snacks, and digital scales.; Comp: Attendance at a Baby Café 1-5 times postnatally; Analysis adjusted for race and/or ethnicity: No | HMF Duration; BF duration of at least 12 mo (AAP goal), Int vs Comp (MA and TX sites combined); 70% vs 30%, p=0.0023 | Meeting HMF Goals; Met or exceeded personal BF duration goal (MA and TX sites separately)
Lewkowitz, 2018 ^162^; LIFE-Moms consortium; RCT-Parallel; n = 59 (Int) and 59 (Comp) | African American: 100%; SES: All socioeconomically disadvantaged; Location: St. Louis, MO | Int: Home-based parenting support and child development educational intervention with additional content on BF, positive eating, and physical activity, delivered biweekly prenatally by trained parent educators; Comp: Home-based parenting support and child development educational intervention, delivered biweekly prenatally by trained parent educators; Analysis adjusted for race and/or ethnicity: No | | HMF Initiation; BF initiation
Li, 2019 ^163^; NHANES 2005-2014; Repeated CS; n = Years 2000-2008: 2,289 (Int) and 481 (Comp); Years 2009-2014: 1,340 (Int) and 198 (Comp) | Years 2000-2008; Years 2009-2014:; Mexican American: 36%; 27%; Non-Hispanic Black: 22%; 28%; Non-Hispanic White: 25%; 23%; Other Hispanic: 9%; 13%; Other Races: 7%; 10%; SES: WIC-eligible individuals; Location: U.S. National Sample | Int: Participation in WIC postnatally; Comp: No participation in WIC postnatally (propensity score matched); Analysis adjusted for race and/or ethnicity: Yes (used to estimate propensity scores) | HMF Initiation; Ever BF, Int vs Comp (ref); 2000-2008: 0.66 vs 0.74, Mean diff (SE): −0.08 (0.03), p<0.05; HMF Duration; BF at 6 mo, Int vs Comp (ref); 2000-2008: 0.40 vs 0.51, Mean diff (SE): −0.11 (0.04), p<0.05; 2009-2014: 0.32 vs 0.45, Mean diff (SE): −0.13 (0.08), p<0.05 | HMF Initiation; Ever BF (2009-2014)
Lovera, 2010 ^164^; NRCT; n = 101 (Int) and 99 (Comp) | Hispanic: 100%; SES: WIC participants; Location: Brownsville, TX | Int: WIC peer counseling prenatally and postnatally for fathers to encourage assistance by fathers in promoting BF and increasing BF initiation and duration, in addition to peer counseling for mothers; Comp: WIC peer counseling for mothers; Analysis adjusted for race and/or ethnicity: No | | HMF Duration; BF duration ≥ 6 mo
Lutenbacher, 2018 ^166^; RCT-Parallel; n = 76-91 (Int) and 70-87 (Comp) | Hispanic: 100%; SES: Predominantly low-income; Location: Large metropolitan area in TN | Int: Home visiting program (Maternal Infant Health Outreach Worker program) by trained peer mentors (five 1-h visits) and printed educational materials after each visit (5 times) from pregnancy to 6 mo postpartum; Comp: Printed educational materials only (5 times) from pregnancy to 6 mo postpartum (minimal education); Analysis adjusted for race and/or ethnicity: No | Exclusive HMF Duration; EBF Duration, Int vs Comp, Median (IQR); 1.4 (0-6) wk vs 0.3 (0-2) wk, p=0.005; BF Exclusivity, Int vs Comp; Overall p=0.011; Never: 55.6% vs 79.1%, p<0.05; Stopped by 2 wk postpartum: 23.3% vs 11.6%, p<0.05; Stopped by 2 mo Postpartum: 18.9% vs 8.1%, p<0.05 | HMF Initiation; Ever breastfed; HMF Duration; BF Status (never and at 2 wk, 2 mo, and 6 mo); BF Duration; Exclusive HMF Duration; BF Exclusivity (Still exclusive 6 mo postpartum)
Lutenbacher, 2022 ^165^; RCT-Parallel; n = 56-59 (Int) and 49-54 (Comp) | Hispanic: 100%; SES: Low-income; Location: Middle TN | Int: Home visiting program (Maternal Infant Health Outreach Worker program; monthly) and periodic group meetings with community health workers (some visits/meetings moved online) with minimal education prenatally through 15 mo postpartum; Comp: Minimal education; Analysis adjusted for race and/or ethnicity: No | HMF Duration; Currently BF, Int vs Comp at 9 mo: 42.9% vs 24.5%, p=0.042 at 12 mo: 36.8% vs 13.2%, p=0.004 | HMF Initiation; BF Initiation; HMF Duration; Currently BF at 2 wk, 2 mo, 6 mo, 15 mo
Martinez-Brockman, 2018a ^168^; Lactation Advice thru Texting Can Help (LATCH); RCT-Parallel; n = 67-71 (Int) and 56-62 (Comp) | Hispanic: 75%; Non-Hispanic: 25%; SES: WIC participants; Location: CT | Int: Peer counseling support program with web-based texting BF support with WIC peer counselors during pregnancy and postpartum; Comp: Peer counseling support program during pregnancy and postpartum; Analysis adjusted for race and/or ethnicity: No | | HMF Duration; Partial BF or EBF at 3 mo; Exclusive HMF Duration; EBF at 2 wk and 3 mo
Martinez-Brockman, 2018b ^167^; Lactation Advice thru Texting Can Help (LATCH); PCS; n = 61 | Hispanic: 73%; Non-Hispanic: 27%; SES: WIC participants; Location: CT | Int: Higher engagement of WIC web-based texting BF support (total postpartum BF issues addressed or number of two-way message exchanges); Comp: Lower engagement of WIC web-based texting BF support (total postpartum BF issues addressed or number of two-way message exchanges); Analysis adjusted for race and/or ethnicity: No | Exclusive HMF Duration; EBF at 2 wk, OR (95% CI); Intensity of engagement: 1.69 (1.12, 2.57), p<0.05 | Exclusive HMF Duration; EBF at 2 wk (total postpartum two-way message exchanges)
Mersky, 2021 ^169^; RCT-Parallel and NRCT; n = 69 (Int), 61 (Int 2), 85 (Comp) | African American/Black: 47%; Hispanic: 41%; Other: 12%; SES: Low-income; Location: Milwaukee, WI | Int: Home visits once per wk prenatally and postnatally, 1h visits, until 6 mo of age; counseling on maternal and child health, parenting practices, child development, school readiness; Int 2: Home visits once every 2 wk prenatally and postnatally, 1 h visits, until 60 days postpartum; counseling on health and nutrition education, care coordination, screening and assessment; Comp: Did not enroll in home visiting services; Analysis adjusted for race and/or ethnicity: Yes | HMF Initiation; Any BF, Int vs Comp (ref), OR (95% CI); 2.7 (1.1, 7.0), p=0.04 | HMF Initiation; Any BF: Int vs Int 2, Int 2 vs Comp; HMF Duration; BF duration: Int vs Int 2, Int vs Comp, Int 2 vs Comp
Reeder, 2014 ^170^; RCT-Parallel; n = 625 (Int), 625 (Int 2), 635 (Comp) | All Other Races and Ethnicities: ~6%; Native American and Hispanic: ~41%; White and Hispanic: ~20%; White and Non-Hispanic: ~33%; SES: WIC participants; Location: OR | Int: WIC telephone peer counseling at low frequency with peer counselors trained in USDA’s Loving Support curriculum (4 calls: prenatal, 2 wk before EDD, 1 and 2 wk postpartum); Int 2: WIC telephone peer counseling at high frequency with peer counselors trained in USDA’s Loving Support curriculum (low frequency intervention plus calls at 1, 2, 3, and 4 mo postpartum); Comp: Usual care; Analysis adjusted for race and/or ethnicity: Yes | HMF Duration; Non-EBF (partial EBF), Int+lnt 2 vs Comp (ref), Relative Risk (95% CI); All Women; At 1 mo: 1.19 (1.10, 1.27), p<0.01; At 3 mo: 1.22 (1.10, 1.34), p<0.01; At 6 mo: 1.18 (1.03, 1.34), p<0.01; Spanish-Speakers; At 1 mo: 1.16 (1.06, 1.28), p<0.01; At 3 mo: 1.29 (1.13, 1.48), p<0.01; At 6 mo: 1.29 (1.10, 1.51), p<0.01; English-Speakers; At 1 mo: 1.22 (1.09, 1.36), p<0.01; At 3 mo: 1.19 (1.02, 1.38), p<0.05; Risk of Non-EBF (partial EBF) cessation, Int+Int2 vs Comp (ref), Relative Risk (95% CI); All Women: 0.85 (0.75, 0.95), p<0.01; Spanish-Speakers: 0.65 (0.53, 0.79), p<0.01; Exclusive HMF Duration; EBF, Int+Int 2 vs Comp (ref), Relative Risk (95% CI); Spanish-Speakers; At 1 mo: 1.13 (1.00, 1.29), p<0.05 At 3 mo: 1.20 (1.02, 1.42), p<0.05; Risk of EBF cessation, Int+Int2 vs Comp (ref), Relative Risk (95% CI); Spanish-Speakers: 0.78 (0.68, 0.89), p<0.01 | HMF Initiation; BF Initiation (All women, Spanish and English-speaking subgroups); HMF Duration; Non-EBF (partial EBF) at 6 mo for English-Speakers Non-EBF (partial EBF) cessation for English-Speakers; Exclusive HMF Duration; EBF at 1 mo, 3 mo, and 6 mo for All Women and English-Speakers; 6 mo for Spanish-Speakers EBF cessation for All Women and English-Speakers
Reifsnider, 2018 ^171^; RCT-Parallel; n = 61 (Int) and 58 (Comp) | Latina: 100% (Mexican: 98%); SES: WIC participants; Location: Metropolitan area in TX | Int: Prenatal and postpartum home visit counseling (8 times total) by promotoras on infant growth, breastfeeding, nutrition, child development, sleep, physical activity, and safety; Comp: Usual care; Analysis adjusted for race and/or ethnicity: No | | HMF Duration; BF at 1 wk and 2 mo; Mo BF
Rotheram-Fuller, 2017a ^173^; RCT-Parallel; n = 99 (Int) and 104 (Comp) | Korean: % NR; Latina: % NR; SES: Predominantly low-income; Location: Los Angeles County, CA | Int: Home visits by health paraprofessionals (Mentor Mothers) with education on obesity, breastfeeding, depressed mood, and infant growth delivered prenatally and postnatally; Comp: Usual care; Analysis adjusted for race and/or ethnicity: No | | HMF Duration; BF duration up to 6 mo (categories)
Rotheram-Fuller, 2017b ^172^; PCS; n = 77 | Korean: % NR; Latina: % NR; SES: Predominantly low-income; Location: Los Angeles County, CA | Int: Higher amount/frequency of content and practice skills targeted by lay community health workers (Mentor Mothers) during telephone call/home visiting program (4 times during pregnancy, 8 times during postpartum through 6 mo); Comp: Lower amount/frequency of content and practice skills targeted by lay community health workers (Mentor Mothers) during telephone call/home visiting program (4 times during pregnancy, 8 times during postpartum through 6 mo); Analysis adjusted for race and/or ethnicity: No | HMF Duration; BF Duration, Amount/frequency of content, r; Parenting: −0.29, p<0.01; Breastfeeding: 0.28, p<0.01; BF Duration, Amount/frequency of practice skills, r; Attending: 0.24, p<0.05; Relaxation: 0.27, p<0.05 | HMF Duration; BF Duration, Amount/frequency of content on: Daily habits, Depression, Risk reduction, Medical adherence, Crisis; BF Duration, Amount/frequency of practice skills: Assertiveness, Goal setting, Modeling, Monitoring, Praise, Response Cost, Problem solving
Sandy, 2009 ^174^; RCT-Parallel; n = 137 (Int) and 101 (Comp) | Latina: 100% (Dominican: 87%, Puerto Rican: 4%, Mexican: 2%, Salvadoran: 2%, Other Latin American countries: 6%, African American or African <1%); SES: Predominantly low-income and immigrant; Location: New York City, NY | Int: Weekly prenatal and postnatal home visiting program with education on pregnancy and prenatal care, childbirth preparation, infant-feeding methods, and child health and safety, with referrals to community agencies; Comp: Usual care (1-2 prenatal home visits with provision of educational materials); Analysis adjusted for race and/or ethnicity: No | Exclusive HMF Duration; Exclusive BF up to 7 d, Int vs Comp, OR (95% CI); 1.92 (1.05, 3.52), p=NR | HMF Initiation; Any BF
Tussing-Humphreys, 2019 ^175^; Delta Healthy Sprouts Project; RCT-Parallel; n = 21 (Int) and 25 (Comp) | African American: ~96%; White: ~4%; SES: Predominantly low-income (high proportion SNAP and/or WIC recipients); Location: MS (3 rural counties) | Int: “Parents as teachers” program providing monthly home visits prenatally and postnatally that included education on child development, parenting practices, early detection of developmental delays, prevent child abuse, and increase school readiness, as well as maternal weight management and early childhood obesity prevention (including BF and other feeding topics); Comp: “Parents as teachers” program providing monthly home visits prenatally and postnatally that included education on child development, parenting practices, early detection of developmental delays, prevent child abuse, and increase school readiness; Analysis adjusted for race and/or ethnicity: No | | HMF Initiation; Ever BF
Ventura, 2022 ^176^; RCT-Cluster; n = 124 (Int) and 122 (Comp) | Hispanic: 79%; SES: WIC participants; Location: Los Angeles County, CA | Int: Policy, systems, and environmental change strategies for promoting responsive bottle-feeding practices within WIC clinics delivered postnatally; Comp: Usual care; Analysis adjusted for race and/or ethnicity: No | | HMF Duration; Any BF at 3 mo and 6 mo; Exclusive HMF Duration; EBF at 3 mo and 6 mo
Washio, 2017 ^177^; RCT-Parallel; n = 18 (Int) and 18 (Comp) | Puerto Rican: 100%; SES: WIC participants; Location: Philadelphia, PA | Int: Increasing financial incentives for continuing BF for 6 mo ($270 total); Comp: No financial incentives for continuing BF; Analysis adjusted for race and/or ethnicity: No | HMF Duration; % BF, Int vs Comp; At 1 mo: 89% vs 44%, p=0.01; At 3 mo: 89% vs 17%, p<0.001; At 6 mo: 72% vs 0%, p<0.001; Duration of BF, Int vs Comp, Mean (SD); 149 (54) d vs 49 (44) d, p<0.001

* Abbreviations: %, percent; ~, approximately; BF, breastfeeding; CI, confidence interval; Comp, comparator; CS, cross sectional; d, day; EBF, exclusive breastfeeding; h, hour; HMF, human milk feeding; IFPS, Infant Feeding Practices Survey; IBCLC, International Board Certified Lactation Consultant; Int, intervention/exposure; mo, month; NHANES, National Health and Nutrition Examination Survey; NRCT, non-randomized controlled trial; OR, odds ratio; PCS, prospective cohort study; r, correlation coefficient; RCT, randomized controlled trial; ref, reference; SD, standard deviation; SES, socioeconomic status; SNAP, Supplemental Nutrition Assistance Program; USDA, United States Department of Agriculture; vs, versus; WIC, Special Supplemental Nutrition Program for Women, Infants, and Children; wk, week

† The following articles are from the same study or had overlapping study samples: Martinez-Brockman et al 2018a and Martinez-Brockman et al 2018b; Rotheram-Fuller et al 2017a and Rotheram-Fuller 2018b; Gross et al 2009 and Gross et al 2011.

Table 21 Risk of bias for randomized controlled trials examining community-physical/built environment interventions, programs, initiatives, and/or policies and human milk feeding outcomes (Key Question 3)^*^

Article | Randomization | Deviations from intended interventions (effect of assignment) | Missing outcome data | Outcome measurement | Selection of the reported result
Cloutier, 2018^153^ | SOME CONCERNS | LOW | HIGH | SOME CONCERNS | HIGH
Harari, 2018^159^ | LOW | LOW | SOME CONCERNS | HIGH | SOME CONCERNS
Lewkowitz, 2018^162^ | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Lutenbacher, 2018^166^ | SOME CONCERNS | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Lutenbacher, 2022^165^ | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS
Martinez-Brockman, 2018a^168^ | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS
Mersky, 2021^169^ | SOME CONCERNS | LOW | SOME CONCERNS | HIGH | SOME CONCERNS
Reeder, 2014^170^ | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS
Reifsnider, 2018^171^ | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS
Rotheram-Fuller, 2017a^173^ | SOME CONCERNS | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Sandy, 2009^174^ | SOME CONCERNS | LOW | SOME CONCERNS | HIGH | SOME CONCERNS
Tussing-Humphreys, 2019^175^ | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS
Washio, 2017^177^ | LOW | LOW | LOW | HIGH | SOME CONCERNS

* Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2016 version)” (August 2019 version)” ( Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ. 2019:366:l4898. doi: 10.1136/bmj.l4898 31462531 )

Table 22 Risk of bias for cluster randomized controlled trials examining community-physical/built environment interventions, programs, initiatives, and/or policies and human milk feeding outcomes (Key Question 3)^*^

Article | Randomization | Timing of identification and recruitment of individual participants in relation to timing of randomization | Deviations from intended interventions (effect of assignment) | Missing outcome data | Outcome measurement | Selection of the reported result
Ventura, 2022^176^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS

* Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2016 version)” (August 2019 version)” ( Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ. 2019:366:l4898. doi: 10.1136/bmj.l4898 31462531 )

Table 23 Risk of bias for non-randomized controlled trials and quasi-experimental studies examining community-physical/built environment interventions, programs, initiatives, and/or policies and human milk feeding outcomes (Key Question 3)^*^

Article | Confounding | Selection of participants | Classification of interventions | Deviations from intended interventions | Missing data | Outcome measurement | Selection of the reported result
Edmunds, 2017^154^ | SERIOUS | LOW | LOW | LOW | MODERATE | LOW | MODERATE
Gabbe, 2017^155^ | SERIOUS | LOW | SERIOUS | LOW | SERIOUS | SERIOUS | MODERATE
Gross, 2009^157^ | SERIOUS | LOW | LOW | LOW | LOW | LOW | MODERATE
Gross, 2011^158^ | SERIOUS | LOW | LOW | LOW | MODERATE | LOW | MODERATE
Harris-Luna, 2018^160^ | SERIOUS | LOW | LOW | LOW | LOW | MODERATE | MODERATE
Lovera, 2010^164^ | MODERATE | LOW | LOW | LOW | LOW | MODERATE | MODERATE
Mersky, 2021^169^ | SERIOUS | LOW | LOW | LOW | SERIOUS | SERIOUS | MODERATE

* Possible ratings of low, moderate, serious, critical, or no information determined using the “Risk of Bias in Non-randomized Studies of Interventions (ROBINS-I) tool” (https://www.riskofbias.info/welcome/home/current-version-of-robins-i) ( Sterne JAC, Hernán MA, Reeves BC, Savović J, Berkman ND, Viswanathan M, Henry D, Altman DG, Ansari MT, Boutron I, Carpenter JR, Chan AW, Churchill R, Deeks JJ, Hróbjartsson A, Kirkham J, Jüni P, Loke YK, Pigott TD, Ramsay CR, Regidor D, Rothstein HR, Sandhu L, Santaguida PL, Schünemann HJ, Shea B, Shrier I, Tugwell P, Turner L, Valentine JC, Waddington H, Waters E, Wells GA, Whiting PF, Higgins JPT. ROBINS-I: a tool for assessing risk of bias in non-randomized studies of interventions. BMJ 2016; 355; i4919; doi: 10.1136/bmj.i4919.27733354 )

Table 24 Risk of bias for observational studies examining community-physical/built environment interventions, programs, initiatives, and/or policies and human milk feeding outcomes (Key Question 3)^*^

Article | Confounding | Selection of participants | Classification of exposures | Deviations from intended exposures | Missing data | Outcome measurement | Selection of the reported result
Caine, 2012^151^ | SERIOUS | LOW | LOW | LOW | MODERATE | MODERATE | SERIOUS
Campbell, 2014^152^ | SERIOUS | LOW | MODERATE | LOW | MODERATE | MODERATE | MODERATE
Gleason, 2020^156^ | MODERATE | LOW | LOW | LOW | NO INFORMATION | MODERATE | MODERATE
Jenkins, 2020^161^ | SERIOUS | LOW | MODERATE | LOW | LOW | MODERATE | MODERATE
Li, 2019^163^ | SERIOUS | LOW | LOW | LOW | NO INFORMATION | MODERATE | MODERATE
Martinez-Brockman, 2018b^167^ | MODERATE | LOW | LOW | LOW | MODERATE | MODERATE | MODERATE
Rotheram-Fuller, 2017b^172^ | SERIOUS | LOW | LOW | LOW | MODERATE | MODERATE | MODERATE

* Possible ratings of low, moderate, serious, critical, or no information determined using the “Risk of Bias for Nutrition Observational Studies” tool (RoB-NObs) ( Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC. )

### NIMHD framework: community level – health care system domain

#### Description of the evidence

This rapid review includes 48 articles (from 47 studies) that were categorized as examining community-health care system interventions, programs, initiatives, or policies.^179–225^ The characteristics and results of each individual article are described in Table 25.

A variety of study designs were used across the body of evidence: 14 were RCT,^182,185,187,188,191,193,195,196,198,207,210,214,216,225^ 1 was a cluster-RCT,^223^ 23 were NRCTs,^183,184,186,189,190,192,199–204,206,208,209,212,213,215,217–221,224^ 2 were quasi-experimental RCS,^179,194^ 1 was a PCS,^181^ and 5 were cross-sectional or repeated cross-sectional studies.^180,197,205,211,222^ Data sources included across the articles were predominantly unnamed but included the Los Angeles County WIC Survey 2008,^205^ 2014,^211^ and 2017,^197^ the Pregnancy Risk Assessment Monitoring System (PRAMS) 2004-2006 (nine states),^180^ 2009-2010 (Minnesota),^204^ and 2012-2014 (New Mexico),^222^ the WIC Infant and Toddler Feeding Practices Study 2 (ITFPS-2),^181^ the Communities and Hospitals Advancing Maternity Practices (CHAMPS) study,^183,209^ the Starting Early study,^191^ the Doula Care Project,^212^ the Nutrition, Exercise, and coping Skills Training (NEST) study,^223^ the Navigating New Motherhood study,^208^ the Provider Approaches to Improved Rates of Infant Nutrition and Growth Study (PAIRINGS),^182^ and the Best Infant Nutrition of Good Outcomes (BINGO) study.^182^ Sample sizes ranged from 31^186^ to 52,790^183^ total participants.

The studies were conducted in a variety of locations across the United States, including the Midwest,^179,187,193,199,202,204,208,220^ the Northeast,^182,184–186,189,191,196,198,200,203,206,210,214,216,217,219^ the Southeast,^183,192,194,201,207,209,213,215,218,221,223^ the Southwest,^190,195,222,224^ the West and West Coast,^188,197,205,211,212,225^ and nationally.^180,181^ Very few studies were conducted specifically in rural areas.^215,225^ Although some studies were conducted with populations representative of the general population or that were economically diverse,^180,182,183,194,201,209,222^ the majority of studies sampled individuals who were predominantly of lower SES such as individuals with low-income or who were WIC-eligible.^179,181,182,184–189,191–193,195–200,202–208,210–220,223–225^ A large proportion of the studies were conducted with participants from a variety of racial and/or ethnic backgrounds. Several were conducted with participants who were predominantly or exclusively Asian or Pacific Islanders,^206,221^ Black and/or African American,^187,192,200,202,210,213,216^ or Hispanic and/or Latino.^185,188,191,195,197,205,207,211,214,215,218,220,224,225^ The studies primarily described participants as women or mothers; this terminology is used throughout this section, as appropriate.

The studies examined a variety of community-health care system, initiatives, and policies. Eleven articles (from ten studies) assessed the impact of Baby-Friendly hospital practices.^180,181,183,189,194,197,203,205,209,211,222^ Four of these studies examined the association between giving birth in a Baby-Friendly designated hospital^194,211^ or a hospital implementing a Baby-Friendly Hospital Initiative^183,203,209^ and human milk feeding outcomes, while six studies examined the impact of individual, Baby-Friendly practices implemented by hospitals or experienced by individuals.^180,181,189,197,205,222^ Eleven studies assessed group-based prenatal and/or postpartum interventions,^179,184,191,198,201,202,213,215,218,223,224^ four of which assessed the CenteringPregnancy group-based care program^184,202,213,218^; the remaining group-based programs were diverse but also focused on education and/or social support.^179,191,198,201,215,223,224^ Most group-based interventions included components delivered both prenatally and postnatally,^184,191,198,202,213,218,223,224^ although three were delivered exclusively during the prenatal period.^179,201,215^ Twenty-two studies examined the impact of individual-focused breastfeeding education, counseling, and/or support.^182,185–188,190,192,193,195,196,199,204,206–208,212,214,216,219–221,225^ The interventions and programs assessed in these studies primarily included components delivered prenatally and postnatally,^182,185,187,188,193,199,204,206–208,214,220^ or only components delivered postnatally^186,190,195,196,212,216,221,225^; two studies assessed interventions or programs that included only components delivered prenatally.^192,219^ These individual-focused interventions and programs were delivered by a variety of providers including nurses,^190,216^ doulas,^187,192,193,204,212^ lactation consultants,^182,206,207,214,220^ peer counselors,^185,199,207,208,216^ social workers,^196^ and health counselors/educators.^186,188,195,206^ The remaining three studies examined other interventions including a postnatal safe-sleep intervention,^210^ a postnatal swaddling intervention,^200^ and an obstetrics and gynecology resident lactation curriculum.^217^

Twenty-six studies examined human milk feeding or exclusive human milk feeding initiation,^179,182,183,185,187–194,198,199,201–204,208,209,213,215,217–221^ 32 studies examined human milk feeding duration,^180,182,184–191,193,196–201,205,206,208,210–213,216,218–220,222–225^ 19 studies examined exclusive human milk feeding duration,^182,185,188–191,195–197,205–208,211,213,214,217,219,223^ and 2 studies examined the outcome of meeting human milk feeding goals.^181,220^

#### Evidence synthesis

Forty-seven studies (from 48 articles) examined community-health care system interventions, programs, initiatives, or policies,^179–225^ 33 of which detected significant impacts on human milk feeding outcomes.^179–184,187,189,191,192,194–199,201–209,211–213,215–217,220,222,223^ More specifically, 17 of 26 studies reported significant, favorable impacts on human milk feeding initiation,^179,182,183,185,187–194,198,199,201–204,208,209,213,215,217–221^ 16 of 32 studies reported significant, favorable impacts on human milk feeding duration,^180,182,184–191,193,196–201,205,206,208,210–213,216,218–220,222–225^ 11 of 19 studies reported significant favorable impacts on exclusive human milk feeding duration,^182,185,188–191,195–197,205–208,211,213,214,217,219,223^ and 1 of 2 studies reported significant favorable impacts on meeting one’s own human milk feeding goal.^181,220^

Beneficial impacts were detected across broad categories of interventions and policies. All 10 studies that examined Baby-Friendly hospital practices reported 1 or more positive impacts on human milk feeding outcomes.^180,181,183,189,194,197,203,205,209,211,222^ Among these studies, benefits were observed across all outcomes assessed including human milk feeding initiation (4 of 4 studies),^183,189,194,203,209^ human milk feeding duration (4 of 6 studies),^180,189,197,205,211,222^ and exclusive human milk feeding duration (3 of 4 studies).^189,197,205,211^ Although overall there were positive impacts of Baby-Friendly hospital practices, within studies there was some variation in results by individual practice and/or by race and/or ethnicity, such that while results were typically positive there were instances of null or negative results by practice or race and/or ethnicity. Group-based interventions also tended to show consistent benefits on human milk feeding outcomes as a whole (8 of 11 studies).^179,184,191,198,201,202,213,215,218,223,224^ Among the group-based interventions, the specific outcomes positively impacted varied across studies, with three of eight studies reporting significant results for human milk feeding initiation,^179,191,198,201,202,213,215,218^ four of eight studies reporting significant results for human milk feeding duration,^184,191,198,201,213,218,223,224^ and three of three studies reporting significant results for exclusive human milk feeding duration.^191,213,223^ The least consistent benefits were observed for individual-focused interventions, which were delivered by providers such as nurses, doulas, lactation consultants, peer counselors, social workers, and health counselors/educators, with 13 of 22 studies reporting 1 or more positive impacts on human milk feeding outcomes.^182,185–188,190,192,193,195,196,199,204,206–208,212,214,216,219–221,225^ The specific outcomes positively impacted varied across studies: 8 of 13 studies reported positive impacts on human milk feeding initiation,^182,185,187,188,190,192,193,199,204,208,219–221^ 8 of 16 studies reported positive impacts on human milk feeding duration,^182,185–188,190,193,196,199,206,208,212,216,219,220,225^ and 4 of 11 studies reported positive impacts on exclusive human milk feeding duration.^182,185,188,190,195,196,206–208,214,219^ The remaining interventions assessed were dissimilar from each other and the other interventions and programs assessed, limiting comparisons.

The evidence was assessed using the following domains:

- [underlined: Consistency]: Looking across studies, the majority reported a positive effect or impact on one or more human milk feeding outcome. However, the specific human milk feeding outcomes that were positively impacted within studies varied. The area of greatest consistency within the body of evidence was for Baby-Friendly hospital designations, initiatives, and practices; this was particularly the case for Black women, whereas the evidence among Hispanic women or other diverse racial and/or ethnic groups was less consistent. Group-based interventions also had relatively consistent benefits on human milk feeding outcomes. Individual-based interventions delivered by persons such as doulas, lactation consultants, and peer counselors had less consistent results; however, this is potentially due to the wider range of interventions and programs assessed.
- [underlined: Precision]: Sample size varied across the studies, ranging from small (<50 participants) to large (>1,000 participants). Significant and non-significant results were observed across study sizes, although the smallest studies tended to report null results.
- [underlined: Risk of bias]: There were several risk of bias concerns across the studies (see Table 26, Table 27, Table 28, Table 29). Among RCT, all studies were assessed as having some concerns or high risk of bias due to missing outcome data, outcome measurement, and selection of reported result, while half of the studies had some concerns due to randomization. Among NRCT and quasi-experimental studies, most were assessed as having serious risk of bias due to confounding and moderate risk of bias due to selection of the reported result. Approximately half of the NRCT and quasi-experimental studies were assessed as having moderate or serious risk of bias due to missing data and outcome measurement, and in a few cases not enough information was provided to assess those domains. Among observational studies, all were assessed as having moderate risk of bias due to outcome measurement and selection of reported result, while most were assessed as having serious risk of bias due to confounding. Further, most studies were assessed as having moderate risk of bias due to classification of exposures while most studies were assessed as having moderate risk of bias due to missing data or did not provide enough information to assess missing data sufficiently.
- [underlined: Directness]: The studies generally aligned with the population, intervention/exposure, comparator, and outcome in the analytic framework. However, one study was less direct, examining a safe sleep practices intervention; in contrast to other studies, a lack of significant impact on breastfeeding duration in this study was interpreted as a positive outcome.^210^
- [underlined: Generalizability]: Most studies were conducted with individuals predominantly or exclusively of lower SES, limiting generalizability to this subset of the population for most interventions and exposures. The racial and/or ethnic composition of the studies varied, with many studies enrolling participants from several racial and/or ethnic groups. Across studies, enrolled participants were most commonly Hispanic, Latina, Black, or African American women. Although women of other races and ethnicities were included in several studies, they were less commonly or prominently represented. Very few studies were explicitly conducted in rural locations, with most studies conducted in cities and the greater metropolitan areas of cities, or instead utilizing data from statewide or national samples.

#### Summary statement

Evidence suggests that community-health care system interventions, programs, initiatives, and policies, including Baby-Friendly hospital practices and group-based programs, may be associated with more favorable human milk feeding outcomes in populations predominantly consisting of individuals from U.S. racial and ethnic minority groups. Among the interventions, programs, initiatives, and policies assessed, the evidence is most consistent for Baby-Friendly hospital practices. The evidence is predominantly generalizable to women who are Hispanic, Latina, Black, or African American and, apart from studies that examined Baby-Friendly hospital practices, to women with a lower socioeconomic status. The evidence was limited by several risk of bias concerns across all study designs.

Table 25 Evidence for community-health care system interventions, programs, initiatives, and/or policies and human milk feeding outcomes (Key Question 3)^*^,^†^

Study | Study Participants | Intervention and Comparator; Adjustment for Race and/or Ethnicity | Significant Results | Non-Significant Results
Ahlers-Schmidt, 2020 ^179^; RCS; n = 299 (Int) and 1,190 (Comp) | Hispanic: 26%; Non-Hispanic Black: 22%; Non-Hispanic White: 48%; Other: 4%; SES: Predominantly low-income; Location: Urban Midwest county (KS) | Int: Baby Talk prenatal group education program (six, 2 h sessions) taught by nurses at clinics; Comp: Propensity score matched women not enrolled in Baby Talk; Analysis adjusted for race and/or ethnicity: Yes (used to estimate propensity scores) | HMF Initiation; BF Initiation, Int vs Comp; Non-Hispanic White: 96.15% vs 89.83%, p<0.05; Non-Hispanic Black: 91.03% vs 77.02%, p<0.05 | HMF Initiation; BF Initiation (Hispanic, Other)
Ahluwalia, 2012 ^180^; PRAMS 2004-2006; Repeated CS; n = 23,356 | Black: 11%; Hispanic: 16%; Other: 9% (not included in analysis); White: 64%; SES: General population; Location: Nine States (CO, FL, IL, LA, ME, NY (including NYC), OR, VT, WV) | Int: Exposure to BF-friendly maternity care practices (primarily Baby-Friendly Hospital practices); Comp: No exposure to BF-friendly maternity care practices; Analysis adjusted for race and/or ethnicity: No | HMF Duration; BF to ≥10 wk, OR (95% CI); Help mothers initiate BF within the 1st h after birth vs Not; Black: 1.62 (1.20, 2.19); White: 1.36 (1.16, 1.58); Give newborn breast milk only vs Not; Black: 2.78 (2.06, 3.75); Hispanic: 2.14 (1.70, 2.70); White: 2.45 (2.19, 2.92); BF on demand vs Not; Black: 1.72 (1.28, 2.31); Hispanic: 1.49 (1.15, 1.91); Baby given a pacifier ([underlined: not] a Baby-Friendly Hospital practice) vs Not; Black: 0.58 (0.44, 0.77); White: 0.76 (0.66, 0.87); Hospital gave gift pack with formula ([underlined: not] a Baby-Friendly Hospital practice) vs Not; Hispanic: 0.67 (0.50, 0.90); Hospital staff helped me learn how to BF vs Not; Black: 0.63 (0.46, 0.88); White: 0.72 (0.59, 0.88); Telephone support vs Not; Black: 1.45 (1.00, 2.72) | HMF Duration; BF to ≥10 wk:; Help mothers initiate BF within 1st h after birth (Hispanic); Infant rooms in with mother (Black, Hispanic, White); BF on demand (White); Baby given pacifier (Hispanic); Hospital gave gift pack with formula (Black, White); Hospital staff gave information on BF (Black, Hispanic, White); Hospital staff helped me learn how to BF (Hispanic); Telephone support (Hispanic, White)
Beauregard, 2022 ^181^; WIC ITFPS-2; PCS; n = 1,080 | Hispanic: 57%; Non-Hispanic Black or African American: 12%; Non-Hispanic White: 25%; Other: 6% (Weighted %); All women with reported intention to EBF to at least 1 mo; SES: WIC participants; Location: U.S. National Sample (27 States) | Int: Exposure to Baby-Friendly Hospital practices; Comp: No exposure to Baby-Friendly Hospital practices; Analysis adjusted for race and/or ethnicity: Yes | Met HMF Goals; Met Intention to EBF Through at Least 1 mo, Risk Ratio (95% CI); Initiated BF Within 1 h of Birth vs Not (ref); 1.3 (1, 1.6), p=0.03; No Food or Drinks Other Than BM vs Not (ref); 4.4 (3.4, 5.7), p<0.0001; Total Number of Baby-Friendly Steps Experienced Consistent with Baby-Friendly Ten Steps to Successful BF; 3 vs 0-2 (ref): 1.7 (1.1, 2.7), p=0.02; 4 vs 0-2 (ref): 3.0 (2.1, 4.4), p<0.0001; 5 vs 0-2 (ref): 4.1 (2.8, 6.0), p<0.0001; 6 vs 0.2 (ref): 4.7 (3.1, 7.0), p<0.0001 | Met HMF Goals; Met BF Intention to EBF Through at Least 1 mo (Show mothers how to BF or maintain lactation even if separated, Rooming-in, BF on demand, No pacifiers given)
Bonuck, 2014 ^182^; Provider Approaches to Improved Rates of Infant Nutrition & Growth Study (PAIRINGS); RCT-Parallel; n = ~129 (Int) and ~133 (Comp) | Biracial/multiracial/other: 8%; Hispanic: 56%; Non-Hispanic Asian: 3%; Non-Hispanic Black: 29%; Non-Hispanic White: 5%; SES: Economically diverse; Location: Bronx, NY | Int: Electronic prompt counseling (sets of 2-3 open-ended questions aimed at portraying BF as the norm, delivered during 5 prenatal visits) and lactation consultations (2 prenatal, 1 hospital visit, and regular phone calls until 3 mo postpartum or BF ceased).; Comp: Usual care; Analysis adjusted for race and/or ethnicity: No | HMF Duration; Any BF, Int vs Comp (ref), OR (95% CI); At 1 mo: 2.79 (1.46, 5.32), p=0.002; At 3 mo: 1.93 (1.17, 3.19), p=0.01; At 6 mo: 1.77 (1.03, 3.07), p=0.04; Exclusive HMF Duration; EBF, Int vs Comp (ref), OR (95% CI); At 1 mo: 4.29 (1.94, 9.47), p<0.001; At 3 mo: 2.86 (1.21, 6.76), p=0.02 | HMF Initiation; BF Initiation; Exclusive HMF Duration; EBF at 6 mo
Bonuck, 2014 ^182^; The Best Infant Nutrition for Good Outcomes (BINGO) Study; RCT-Parallel; n = ~238 (Int), ~236 (Int 2), ~77 (Int 3), and ~77 (Comp) | Biracial/multiracial/other: 8%; Hispanic: 57%; Non-Hispanic Asian: 2%; Non-Hispanic Black: 29%; Non-Hispanic White: 4%; SES: Predominantly low-income; Location: Bronx, NY | Int: Electronic prompt counseling (sets of 2-3 open-ended questions aimed at portraying BF as the norm, delivered during 5 prenatal visits) and lactation consultations (2 prenatal, 1 hospital visit, and regular phone calls until 3 mo postpartum or BF ceased).; Int 2: Electronic prompt counseling only; Int 3: Lactation consultations only; Comp: Usual care; Analysis adjusted for race and/or ethnicity: No | HMF Initiation; BF Initiation, Int vs Comp (ref); 3.29 (1.03, 10.48), p=0.04; HMF Duration; Any BF, Int vs Comp (ref), OR (95% CI); At 1 mo: 2.10 (1.20, 3.67), p=0.009; At 3 mo: 2.10 (1.23, 3.61), p=0.007; Exclusive HMF Duration; EBF, Int vs Comp (ref), OR (95% CI); At 3 mo: 4.24 (1.01, 37.94), p=0.05 | HMF Initiation; BF Initiation, Int 2 vs Comp & Int 3 vs Comp; HMF Duration; Any BF at 1 mo, 3 mo, 6 mo, Int 2 vs Comp, Int 3 vs Comp; Any BF at 6 mo, Int vs Comp; Exclusive HMF Duration; Exclusive BF at 1 mo, 3 mo, 6 mo, Int 2 vs Comp, Int 3 vs Comp; EBF at 1 mo, 6 mo, Int vs Comp
Burnham, 2022 ^183^; Mississippi Communities and Hospitals Advancing Maternity Practices (CHAMPS); NRCT (Before and After Study); n = 31,329 | Black (Non-Hispanic): 47%; Other: 1%; White (Non-Hispanic): 51% (All median % across participating hospitals); SES: General population; Location: MS | Int: Implementation of Baby-Friendly Hospital practices through CHAMPS initiative (over 49 mo); Comp: Earlier in implementation process; Analysis adjusted for race and/or ethnicity: Yes | HMF Initiation; BF Initiation,; Change per mo, Relative Risk (95% CI); Overall: 1.004 (1.002, 1.005), p<0.001; Black (Non-Hispanic): 1.006 (1.004, 1.009), p<0.001; White (Non-Hispanic): 1.002 (1.001, 1.003), p<0.001; 49th mo vs 1st mo (ref),; Overall: 66% vs 56%, 10% point increase, p<0.05; Black (Non-Hispanic): 21% point increase, p<0.05; White (Non-Hispanic): 4% point increase, p<0.05; Change in Black-White Disparity per mo, Relative Risk (95% CI); -0.176% point (−0.060, −0.292), p=0.003; EBF at Hospital, Change per mo, Relative Risk (95% CI); Overall: 1.005 (1.002, 1.008), p<0.001; Black (Non-Hispanic): 1.009 (1.004, 1.015), p=0.001; White (Non-Hispanic): 1.003 (1.000, 1.007), p=0.04 | HMF Initiation; EBF at Hospital (Change in Black-White Disparity per mo)
Chae, 2017 ^184^; NRCT; n = 100 (Int) and 157 (Comp) | Asian: ~16%; African American: ~24%; Latina: ~33%; White: ~27%; Other: ~1%; SES: Predominantly low-income, eligible for Medicaid; Location: NJ | Int: Group-based prenatal care (CenteringPregnancy) consisting of 10, 2 h sessions starting at 16-18 wk gestation, and one postpartum ‘reunion’ session. Sessions include self-care skills, basic health information, provider assessments, and group sharing of concerns, support.; Comp: Usual care; Analysis adjusted for race and/or ethnicity: No | HMF Duration; BF at postpartum visit (~6-8 wk, but could be several mo later due to scheduling issues), Int vs Comp (ref), OR (95% CI); 2.95 (1.73, 5.04)
Chapman, 2013 ^185^; RCT-Parallel; n = 55-76 (Int) and 53-78 (Comp) | African American: ~10%; Hispanic: ~82%; Other: ~3%; White: ~5%; 100% with overweight or obesity; SES: Low-income (all <185% of federal poverty level); Location: Hartford, CT | Int: Specialized BF peer counseling (3 prenatal visits, daily hospital visits after delivery, and up to 11 postpartum home visits); Comp: Usual care; Analysis adjusted for race and/or ethnicity: No | | HMF Initiation; BF Initiation; HMF Duration; Any BF at 2 wk, 1 mo, 2 mo, 3 mo, 4 mo, 5 mo, and 6 mo; Exclusive HMF Duration; EBF since birth at 1 d, 2 wk, 1 mo, 2 mo, 3 mo, 4 mo, 5 mo, at 6 mo
Disantis, 2010 ^186^; NRCT; n = 16 (Int) and 15 (Comp) | African American: 25%; Hispanic: 50%; Other Races/Ethnicities NR; 100% current smokers or recent ex-smokers (<1 y); SES: Low-income; Location: Philadelphia, PA | Int: Smoking relapse prevention plus breastfeeding counseling, delivered in hospital’s postpartum unit by behavioral health counselor within 72 h of birth. Session consisted of 15 min of individual health counseling plus relevant take-home materials.; Comp: Smoking relapse prevention counseling only (15 min).; Analysis adjusted for race and/or ethnicity: No | | HMF Duration; BF duration assessed at 1 mo
Edwards, 2013 ^187^; RCT-Parallel; n = 108-122 (Int) and 113-123 (Comp) | African American: 100%; SES: Predominantly low income, Medicaid recipients; Location: Chicago, IL | Int: Prenatal and postpartum intervention (<34 wk gestation through 3 mo postpartum) delivered in the participant’s home (avg: 10 prenatal & 12 postpartum visits) and during delivery by African American doulas. Content focused on relationship development with the mother, BF education, addressing maternal BF concerns, family involvement in BF support; lactation support, 24/7 doula availability.; Comp: Usual care; Analysis adjusted for race and/or ethnicity: No | HMF Initiation; Attempted BF, Int vs Comp, % (95% CI); 63.9 (55.3, 72.5) vs 49.6 (40.7, 58.5), p=0.02; HMF Duration; BF longer than 6 wk, Int vs Comp, 28.7% vs 16.8% (p=0.04) | HMF Duration; BF duration at 4 mo
Efrat, 2015 ^188^; RCT-Parallel; n = 55-125 (Int) and 62-128 (Comp) | Hispanic: 100%; SES: Low-income; Location: Los Angeles County, CA | Int: Telephone-based breastfeeding intervention delivered by lactation educators during third trimester of pregnancy (4 calls) and for 6 mo postpartum (17 calls); Comp: Usual care; Analysis adjusted for race and/or ethnicity: No | | HMF Initiation; BF initiation; HMF Duration; Any BF at 1 mo, 3 mo, 6 mo; Duration of Any BF (total sample and those who initiated BF); Exclusive HMF Duration; EBF at 1 mo, 3 mo, and 6 mo; Duration of EBF (total sample and those who initiated BF)
Ekambaram, 2019 ^189^; NRCT (Before and After Study); n = 152 (Int) and 190 (Comp) | African American: ~62%; Caucasian: ~13%; Hispanic: ~22%; Other: ~3%; SES: Predominantly low-income; Location: Philadelphia, PA | Int: Post-implementation of Baby-Friendly aligned pacifier policy (no pacifiers placed in bassinet, educational messages delivered by nurses to mothers intending to BF on pacifier use); Comp: Pre-implementation of Baby-Friendly aligned pacifier policy (pacifiers placed in all bassinets); Analysis adjusted for race and/or ethnicity: No | HMF Initiation; EBF at Hospital Discharge, Int vs Comp; 51.3% vs 40%, p=0.04 | HMF Duration; Any BF at 1 mo; Exclusive HMF Duration; EBF at 1 mo
Grassley, 2011 ^190^; NRCT; n = 60 (Int) and 46 (Comp) | African American: 19%; Hispanic/Latina: 53%; Mixed/Other: 1%; White: 27%; 100% adolescents; SES: NR; Location: North Central TX | Int: Nurse-provided support focused on age-specific labor support, age-specific BF support, and mother-infant skin-to-skin contact for adolescents; Comp: Usual care; Analysis adjusted for race and/or ethnicity: No | | HMF Initiation; BF at discharge; EBF at discharge; HMF Duration; BF at 6 wk, 3mo; Exclusive HMF Duration; EBF at 6 wk, 3 mo
Gross, 2016 ^191^; Starting Early; RCT-Parallel; n = 221 (Int) and 235 (Comp) | Hispanic/Latina: 100%; SES: Predominantly low income, WIC eligible; Location: New York City, NY | Int: Family-centered primary care-based early child obesity prevention intervention designed for low-income Hispanic families from the third trimester through child age 3 y. Fifteen total group-based sessions including content on individual nutrition counseling, nutrition and parenting support groups, plain language handouts, and nutrition education DVDs, with the first two sessions (1 and 2 mo postpartum) focusing on BF support.; Comp: Usual care; Analysis adjusted for race and/or ethnicity: No | Exclusive HMF Duration; Exclusive BM at 3 mo, Int vs Comp (ref), OR (95% CI); 1.61 (1.07, 2.44) | HMF Initiation; Ever BF in the hospital, Exclusive BM in the hospital, Exclusive BM leaving the hospital; HMF Duration; Any BM at 3 mo
Gruber, 2013 ^192^; NRCT; n = 97 (Int) and 128 (Comp) | African American: 78%; Other: 15%; White: 7%; SES: Predominantly low-income; Location: Greensboro, NC | Int: Eight wk childbirth education classes designed for mothers at risk of adverse birth outcomes with a doula who provided support throughout pregnancy and labor/delivery; Comp: Eight wk childbirth education classes designed for mothers at risk of adverse birth outcomes without doula support; Analysis adjusted for race and/or ethnicity: No | HMF Initiation; BF Initiation, Int vs Comp; All participants: 79.4% vs 67.2%, p<0.03; Adults: 90.2% vs 73.2%, p<0.04 | HMF Initiation; BF Initiation, Adolescents
Hans, 2018 ^193^; RCT-Parallel; n = 139-142 (Int) and 139-141 (Comp) | Black/African American: 45%; Latina/Hispanic: 38%; Multiracial/Other: 9%; White: 8%; SES: Predominantly low-income; Location: IL (Large city and 2 smaller urban areas) | Int: Home visits from a doula and a home visitor (family support worker, parent educator) during pregnancy and postpartum; Comp: Case management control; Analysis adjusted for race and/or ethnicity: No | | HMF Initiation; BF initiation in the hospital; HMF Duration; BF at 3 mo
Hemingway, 2021 ^194^; RCS (Before and After Study); n = 3,606 (Int) and 3,079 (Comp) | Black Non-Hispanic: ~40%; Hispanic: ~20%; Other Ethnicity/Race: ~2%; White Non-Hispanic: ~38%; SES: General population; Location: Southeastern SC | Int: Born in hospital following Baby-Friendly Hospital Initiative implementation (Baby-Friendly USA® hospital designation); Comp: Born in hospital before Baby-Friendly Hospital Initiative implementation; Analysis adjusted for race and/or ethnicity: No | HMF Initiation; BF Initiation, Int vs Comp (ref), Relative Risk (95% CI); All: 81% vs 69%, 1.17 (1.13, 1.19); Black: 66% vs 52%, 1.27 (1.19, 1.35); Non-Black: 90% vs 81%, 1.1 (1.07, 1.13)
Hopkinson, 2009 ^195^; RCT-Parallel; n = 226 (Int) and 241 (Comp) | Hispanic: 100%; Primarily first-generation immigrants and monolingual; Hispanic; 100% mixed feeding at recruitment (20-48 h postpartum); SES: WIC eligible; Location: Houston, TX | Int: Bilingual, bicultural para-professional-delivered intervention including BF history, breast exam, infant oral-motor assessment, weight, latch and milk transfer, maternal concerns and support system; with review of the importance of EBF. Delivered in hospital-based breastfeeding clinic 3-7 d postpartum; Comp: Usual care; Analysis adjusted for race and/or ethnicity: No | Exclusive HMF Duration; EBF at 4wk, Int vs Comp; 16.8% vs 10.4%, p=0.045
Howell, 2014 ^196^; RCT-Parallel; n = 270 (Int) and 270 (Comp) | Black/African American: 38%; Hispanic/Latina: 62%; SES: Predominantly low-income; Location: New York City, NY | Int: Postpartum behavioral educational intervention delivered by social worker (one in-hospital educational session post-delivery, one phone call 2 wk postpartum); Comp: Enhanced usual care (list of community resources and 2-week control call); Analysis adjusted for race and/or ethnicity: No | HMF Duration; BF Duration, Int vs Comp; Median: 12 wk vs 6.5 wk, p=0.019; Likelihood of Quitting BF by 6 mo Postpartum, Int vs Comp; HR (95% CI): 0.79 (0.65, 0.97) | Exclusive HMF Duration; EBF at 6 mo Postpartum
Jung, 2019 ^197^; Los Angeles County WIC Survey 2017; CS; n = 1,544 | Hispanic: 74%; SES: WIC-enrolled families; Location: Los Angeles County, CA | Int: Exposure to Baby-Friendly Hospital practices (1-3 practices: (1) child was fed only human milk at hospital, (2) hospital staff did not give formula to take home, (3) hospital gave telephone number to call for BF help); Comp: No exposure to Baby-Friendly Hospital practices; Analysis adjusted for race and/or ethnicity: Yes | HMF Duration; Any BF; Fed child only HM at hospital vs Not; At 6 mo: 51.1% vs 44.8%, p<0.05; Was NOT given formula to take home vs Was; At 1 mo: 96.8% vs 90.2%, p<0.001; Given phone number to BF helpline vs Not; At 1 mo: 95.0% vs 86.4%, p<0.001; At 3 mo: 58.2% vs 46.7%, p<0.01; At 6 mo: 48.3% vs 36.9%, p<0.01; 1 Baby-Friendly practice vs 0 (ref); At 1 mo: OR (95% CI): 3.03 (1.63, 5.57); 2 or more Baby-Friendly practices vs 0 (ref); At 1 mo: OR (95% CI): 18.03 (8.75, 38.04); At 3 mo: OR (95% CI): 1.94 (1.25, 3.04); At 6 mo: OR (95% CI): 1.71 (1.07, 2.76); Exclusive HMF Duration; EBF; Fed child only HM at hospital vs Not; At 1 mo: 74.2% vs 0%, p<0.001; At 3 mo: 33.8% vs 0%, p<0.001; At 6 mo: 16.7% vs 0%, p<0.001; Was NOT given formula to take home vs Was; At 1 mo: 55.2% vs 43.1%, p<0.001; At 3 mo: 25.3% vs 10.7%, p<0.001; At 6 mo: 12.9% vs 4.7%, p<0.001; Given phone number to BF helpline vs Not; At 1 mo: 43.9% vs 28.7%, p<0.001; At 3 mo: 20.2% vs 12.4%, p<0.05; 2 Baby-Friendly practices vs 0 (ref); At 1 mo: OR (95% CI): 5.67 (3.44, 9.78); At 3 mo: OR (95% CI): 4.68 (2.25, 11.40); At 6 mo: OR (95% CI): 4.48 (1.61, 18.64) | HMF Duration; Fed child only HM at hospital vs Not:; Any BF at 1 mo and 3 mo; Was NOT given formula to take home vs Was:; Any BF at 3 mo and 6 mo; 1 Baby-Friendly practice vs 0:; Any BF at 3 mo and 6 mo; Exclusive HMF Duration; Given phone number to BF helpline vs NOT:; EBF at 6 mo; 1 Baby-Friendly practice vs 0:; EBF at 1 mo, 3 mo and 6 mo
Kao, 2015 ^198^; RCT-Parallel; n = 53 (Int) and 46 (Comp) | African American: 14%; Caucasian: 28%; Hispanic: 44%; Other: 13%; At risk for postpartum depression but not currently receiving mental health care or diagnosed with current major depressive disorder; SES: Receiving public assistance; Location: Inner city, northeast United States | Int: Group, psychoeducational program (ROSE) to prevent postpartum depression by developing emotional and behavioral strategies and strengthening social support (no explicit mention of BF or BF skills). Delivered as four, 60 min group sessions over 4 wk at the prenatal clinic during pregnancy and one, 50 min individual session at home or the clinic soon after delivery.; Comp: Usual care; Analysis adjusted for race and/or ethnicity: No | HMF Duration; BF Duration at 3 mo, Int vs Comp (n=54), Median (SD); 54 (32.5) d vs 21 (31.6) d, p=0.013 | HMF Initiation; BF Initiation
Keenan-Devlin, 2021 ^199^; NRCT (Before and After Study); n = 273 (Int) and 147 (Comp) | Asian: ~10%; Black: ~24%; Latinx: ~34%; Other: ~22%; White: ~9%; SES: Medicaid-enrolled patients; Location: Chicago, IL | Int: Clinically integrated BF peer counseling with contacts during pregnancy, after delivery, and post-discharge, as well as access to monthly educational classes, weekly support groups, and phone “warmline”; Comp: No BF peer counseling program (baseline); Analysis adjusted for race and/or ethnicity: No | HMF Initiation; BF Initiation, Int vs Comp (ref); Other: 100% vs 87%, p=0.04; EBF During Hospital Stay, Int vs Comp; Total: 32% vs 21%, p=0.03; HMF Duration; Any BF at 6 wk, Int vs Comp; Total: 65% vs 41%, p<0.01; Asian: 74% vs 40%, p=0.04; Black: 50% vs 32%, p<0.01; Latinx: 70% vs 37%, p<0.01; White: 39% vs 18%, p=0.01 | HMF Initiation; BF Initiation (Total, White, Black, Asian, Latinx), EBF During Hospital Stay (White, Black, Other, Asian, Latinx); HMF Duration; Any BF at 6 wk (Other)
Kelly, 2017 ^200^; NRCT (Before and After Study); n = 40 (Int) and 121 (Comp) | African American: ~78%; Latino: ~14%; Other: ~7%; White: ~1%; SES: Predominantly have public insurance; Location: Philadelphia, PA | Int: Postpartum swaddling education; Comp: Usual care; Analysis adjusted for race and/or ethnicity: No | | HMF Duration; BF at 2 mo
Kettrey, 2020 ^201^; NRCT; n = 90 (Int) and 810 (Comp) for Site A; 39 (Int) and 585 (Comp) for Site C; 20 (Int) and 28 (Comp) for Site E | Black/African American: 0% (Site A), 16% (Site C), NR (Site E); Hispanic: 1% (Site A), 82% (Site C), 90% (Site E); White: 100% (Site A), 58% (Site C), NR (Site E); SES: Varying SES levels across study sites; Location: TN (Site A: Rural; Site C: Urban; Site E: Rural) | Int: March of Dimes Supportive Pregnancy Care program which includes ten group-based, 90-120 min sessions on social support, health education, and skill building during pregnancy; Comp: Usual care; Analysis adjusted for race and/or ethnicity: Yes (weighting through propensity scores for Sites A and C) | HMF Initiation; BF at delivery, Int vs Comp (ref), OR (95% CI); Site A: 3.25 (1.70, 5.99), p<0.001; HMF Duration; BF at postpartum visit, Int vs Comp (ref), OR (95% CI); Site A (n=537 total): 11.82 (1.60, 87.36), p<0.05 | HMF Initiation; BF at delivery (Site C; Data NR for Site E); HMF Duration; BF at postpartum visit (Site E, n=45 total; Data NR for Site C)
Klima, 2009 ^202^; NRCT; n = 61 (Int) and 207 (Comp) | African American: 100%; SES: Predominantly low-income; all Medicaid eligible; Location: Chicago, IL | Int: Group-based prenatal care (CenteringPregnancy) consisting of 10, 2 h sessions starting at 16-18 wk gestation, and one postpartum session. Sessions include self-care skills, basic health information, provider assessments, and group sharing of concerns, support.; Comp: Usual care; Analysis adjusted for race and/or ethnicity: No | HMF Initiation; BF Initiation (Any BF at discharge), Int vs Comp; 59.0% vs 43.6%, p<0.05; EBF at discharge, Int vs Comp; 44.3% vs 31.2%, p<0.05
Knutson, 2022 ^203^; NRCT (Before and After Study); n = 186 (Int) and 30 (Comp) | Asian: ~4%; Hispanic: ~53%; Non-Hispanic Black: ~24%; Non-Hispanic White: ~18% (Int only; Comp NR); SES: Primarily uninsured or Medicaid insured individuals; Location: Providence, RI | Int: Gave birth during 8 wk implementation period of a Baby-Friendly quality improvement project including infant feeding plan, BF video/teach-back, cue-based feeding log, RN scripts for formula requests, early hand expression instruction, and RN team engagement; Comp: Gave birth before implementation of Baby-Friendly quality improvement project; Analysis adjusted for race and/or ethnicity: No | HMF Initiation; EBF at Hospital Discharge, Int vs Comp; Black: 16% vs 0% (greater change compared to White: p=0.005) | HMF Initiation; EBF at Hospital Discharge (Hispanic, Int vs Comp)
Kozhimannil, 2013 ^204^; MN PRAMS 2009-2010 (control group); NRCT; n = 1,069 (Int) and 51,721 (Comp) | African American: 10% (Int) and 9% (Comp); African Descent: 36% (int) and 9% (Comp); Asian: 6% (Int) and <1% (Comp); Hispanic: 37% (Int) and 15% (Comp); Native American: 1% (Int) and 15% (Comp); Other: <1% (Int) and 6% (Comp); White: 10% (Int) and 58% (Comp); SES: Low-income with Medicaid coverage; Location: MN | Int: Doula-supported, culturally-appropriate care provided by a non-profit organization (Everyday Miracles) during the perinatal period (timing/frequency NR), with improved breastfeeding skills as an explicit goal. Services include prenatal education, continuous labor support, postpartum visits, and breastfeeding education.; Comp: General state Medicaid population; Analysis adjusted for race and/or ethnicity: No | HMF Initiation; BF Initiation, Int vs Comp, % (95% CI); Total: 97.9% (97.0, 98.7) vs 80.8% (78.0, 83.3); African American: 92.7% (87.8, 97.7) vs 70.3% (64.5, 75.5); African Descent: 99.5% (98.8, 100.0) vs 95.2% (82.4, 98.8); Hispanic: 99.2% (98.4, 100.0) vs 92.0% (85.5, 95.8); White: 98.2% (95.6, 100.0) vs 78.7% (74.5, 82.4) | HMF Initiation; BF Initiation (Inadequate sample size: Asian, Native American, Other)
Langellier, 2012 ^205^; Los Angeles County WIC Survey 2008; CS; n = 4,725 | Hispanic: 91%; Non-Hispanic Black: 5%; Non-Hispanic White: 2%; Other/Multi: 2%; SES: WIC participants; Location: Los Angeles County, CA | Int: In-Hospital BF (Baby-Friendly Hospital practice); Int 2: Receipt of Formula Discharge Pack (Hospital practice that is [underlined: not] Baby-Friendly); Comp: No exposure to these hospital practices; Analysis adjusted for race and/or ethnicity: Yes | HMF Duration; Any BF, OR (95% CI); Int: Non-Exclusive In-Hospital BF vs Comp: None (ref); At 6 mo: 4.256 (3.519, 5.148), p<0.01; At 12 mo: 3.523 (2.753, 4.510), p<0.01; At 24 mo: 2.719 (1.644, 4.495), p<0.01; Int: Exclusive In-Hospital BF vs Comp: None (ref); At 6 mo: 9.937 (7.927, 12.46), p<0.01; At 12 mo: 8.043 (6.169, 10.49), p<0.01; At 24 mo: 5.718 (3.435, 9.519), p<0.01; Exclusive HMF Duration; EBF at 6 mo, Int 2: Formula Discharge Pack at Hospital vs Comp: None (ref), OR (95% CI); 0.541 (0.393, 0.744), p<0.01 | HMF Duration; Any BF at 6 mo, 12 mo, and 24 mo (Int 2 - Formula Discharge Pack at Hospital)
Lau, 2021 ^206^; NRCT (Before and After Study); n = 469 (Int) and 1006 (Comp) | Chinese American: 100%; SES: Predominantly low-income; Location: New York City, NY | Int: One-on-one BF education, counseling, and support during third trimester and postpartum in-hospital and via phone by lactation consultants and health educators; Comp: Usual care; Analysis adjusted for race and/or ethnicity: No | HMF Duration; Any BF at 4-6 wk, Int vs Comp; Pre-intervention: 46.4% vs. 52.2%; Post-intervention: 70.7% vs 59.7%; Diff in change: 16.8% points, p<0.01; Program impacts were higher in those using non-Medicaid insurance; lower in those with less education; Exclusive HMF Duration; EBF at 4-6 wk, Int vs Comp; Pre-intervention: 14.2% vs. 16.9%; Post-intervention: 26.9% vs 20.6%; Diff in change: 9.1% points, p<0.05; Program impacts were higher in those using non-Medicaid insurance
Linares, 2019 ^207^; RCT-Parallel; n = 14-20 (Int) and 15-19 (Comp) | Hispanic: 100%; 100% immigrants to the United States; SES: Predominantly WIC participants; Location: Central KY | Int: Individual peer counselor and IBCLC support during pregnancy until 6 mo postpartum (up to 5 hospital and/or home visits with follow-up phone calls); Comp: Usual care; Analysis adjusted for race and/or ethnicity: No | Exclusive HMF Duration; EBF Assessed Over 4 Time Points (discharge, 1 mo, 3 mo, 6 mo, Int vs Comp (ref), OR (95% CI) 3.1 (1.1, 8.7), p<0.05 | Exclusive HMF Duration; EBF (Time Point by Group Interaction)
Martinez, 2020 ^208^; Navigating New Motherhood; NRCT (Before and After Study); n = 99 (Int) and 119 (Comp) | Asian: ~5%; Black Hispanic: ~2%; Non-Hispanic Black: ~49%; Non-Hispanic White: ~13%; Other: <1%; White Hispanic: ~30%; SES: Predominantly low-income; Location: Chicago, IL | Int: One-on-one antenatal and postpartum lactation support with peer counselor at a clinic, at home, and via text; Comp: Before introduction of peer counselor; Analysis adjusted for race and/or ethnicity: No | HMF Initiation; Any BF, Int vs Comp (ref), OR (95% CI); 2.85 (1.11, 7.32), p<0.05 | HMF Duration; BF Continuation at 6 wk and ≥6 mo; Exclusive HMF Duration; EBF at 6 wk
Merewood, 2019 ^209^; Communities and Hospitals Advancing Maternity Practices (CHAMPS); NRCT (Before and After Study); n = 39,272 | African American, Non-Hispanic: 34%; Hispanic: 5%; Other: 3%; White, Non-Hispanic: 46% (All median % across participating hospitals); SES: General population; Location: Southern U.S. States (LA, MS, TN, TX) | Int: Implementation of three or more Baby-Friendly Hospital practices through CHAMPS initiative (at 31 mo and implementation of specific practices); Comp: Earlier in implementation process (at 1 mo); Non-implementation of specific practices; Analysis adjusted for race and/or ethnicity: Yes | HMF Initiation; BF Initiation; 31st mo vs 1st mo; Overall: 75% vs 66%, p< 0.05; African American: 63% vs 46%, p<0.05; African American vs White: Change in disparity (95% CI): −9.6% points (1.6, 19.5); Skin-to-skin care vs Not (ref), among vaginal deliveries, Rate Ratio (95% CI); Overall: 1.09 (1.03, 1.15); Hispanic: 1.21 (1.07, 1.37); Skin-to-skin care vs Not (ref), among cesarean deliveries, Rate Ratio (95% CI); Overall: 1.15 (1.08, 1.23); African American: 1.38 (1.25, 1.53); Hispanic: 1.19 (1.07, 1.32); EBF at hospital; 31st mo vs 1st mo; Overall: 39% vs 34%, p<0.05; African American: 31% vs 19%, p<0.05; Skin-to-skin care vs Not (ref), among vaginal deliveries, Rate Ratio (95% CI); Overall: 1.14 (1.04, 1.25); Skin-to-skin care vs Not (ref), among cesarean deliveries, Rate Ratio (95% CI); Overall: 1.20 (1.07, 1.34); African American: 1.65 (1.31, 2.08); Hispanic: 1.50 (1.18, 1.91); White: 1.10 (1.00, 1.21); Rooming in vs Not (ref), Rate Ratio (95% CI); African American: 1.54 (1.14, 2.07) | HMF Initiation; BF Initiation; 31st mo vs 1st mo (Hispanic, White); Skin-to-skin care vaginal delivery (African American, White); Skin-to-skin care cesarean delivery (White); Rooming in (Overall, African American, Hispanic, White); EBF at hospital; 31st mo vs 1st mo (Hispanic, White); Skin-to-skin care vaginal delivery (African American, Hispanic, White); Rooming in (Overall, Hispanic, White)
Moon, 2017 ^210^; RCT-Parallel; n = 305-456 (Int) and 332-502 (Comp) | African American: 100%; SES: Over half receiving WIC benefits and/or have Medicaid or no insurance; Location: Washington, DC | Int: Enhanced messaging on AAP-recommended safe sleep practices (including roomsharing without bedsharing) for both SIDS risk reduction and suffocation prevention delivered postnatally; Comp: Standard messaging on AAP-recommended safe sleep practices; Analysis adjusted for race and/or ethnicity: No | | HMF Duration; BF duration assessed at 2-3 wk, 2-3 mo, and 5-6 mo
Nobari, 2017 ^211^; Los Angeles County WIC Survey 2014; CS; n = 299 (Int), 764 (Int 2), and 598 (Comp) | Hispanic: 82%; SES: WIC-enrolled families; Location: Los Angeles County, CA | Int: Baby-Friendly designated hospital; Int 2: Baby-Friendly hospital designation in process; Comp: Not Baby-Friendly designated hospital; Analysis adjusted for race and/or ethnicity: Yes | Exclusive HMF Duration; EBF; Int vs Comp (ref); At 1 mo: OR (95% CI): 1.49 (1.09, 2.03); At 3 mo: OR (95% CI): 1.50 (1.04, 2.17); Int 2 vs Comp (ref); At 1 mo: OR (95% CI): 1.47 (1.15, 1.87); At 3 mo: OR (95% CI): 1.38 (1.03, 1.85) | HMF Duration; Any BF at 1 mo, 3 mo, and 6 mo (Int, Int 2); Exclusive HMF Duration; EBF at 6 mo (Int, Int 2)
Nommsen-Rivers, 2009 ^212^; Doula Care Project; NRCT; n = 37 (Int) and 91 (Comp) | African American: 21%; Asian: 8%; Hispanic: 43%; White Non-Hispanic: 29%; 100% Primiparous; SES: Low-income individuals; Location: Sacramento, CA | Int: Doula care in-hospital (during labor, delivery, and after delivery) and two home visits in the first 2 wk postpartum; Comp: Standard of care (no doula available); Analysis adjusted for race and/or ethnicity: Yes | HMF Duration; BF at 6 wk, Int vs Comp (ref), OR (95% CI); With prenatal stressor; 23.76 (3.49, 161.73) | HMF Duration; BF at 6 wk (Overall, Without prenatal stressor)
Patberg, 2021 ^213^; NRCT; n = 40-215 (Int) and 9-120 (Comp) | African American/Black: 98%; SES: All insured through Medicaid or Medicare; Location: Atlanta, GA | Int: Group-based prenatal care (CenteringPregnancy) consisting of 10, 2 h sessions starting at 16-18 wk gestation, and one postpartum ‘reunion’ session. Sessions include self-care skills, basic health information, provider assessments, and group sharing of concerns, support.; Comp: Usual care; Analysis adjusted for race and/or ethnicity: No | HMF Initiation; Any BF at discharge, Int vs Comp (ref), Relative Risk (95% CI); 1.14 (1.03, 1.26), p=0.011; Exclusive HMF Duration; Exclusive BF postpartum (assessment at ~4-12 wk), Int vs Comp (ref), Relative Risk (95% CI); 2.54 (1.29, 4.99), p=0.004; (Note - adjusted analyses not conducted due to small sample size) | HMF Duration; Any BF postpartum (assessment at ~4-12 wk)
Petrova, 2009 ^214^; RCT-Parallel; n = 52 (Int) and 52 (Comp) | Asian: 1%; Black: 6%; Hispanic: 87%; White: 6%; SES: WIC participants; Location: New Brunswick, NJ | Int: One-on-one BF education and support with lactation consultant (two 15-20 min prenatal sessions at hospital and one postnatal session at hospital or by phone); Comp: Usual care; Analysis adjusted for race and/or ethnicity: No | | Exclusive HMF Duration; EBF at 1 wk, 1 mo, 2 mo, and 3 mo
Pitcock, 2021 ^215^; NRCT; n = 35 (Int) and 68 (Comp) | Hispanic: 100%; SES: Low-income and uninsured; Location: Rural VA | Int: Six h group educational intervention (¡Tengo Leche!) delivered by bilingual health educator in third trimester combined with in-hospital peer support following birth; Comp: In-hospital peer support following birth; Analysis adjusted for race and/or ethnicity: No | HMF Initiation; EBF at discharge, Int vs Comp; 46.7% vs 24.6%, p=0.02
Pugh, 2010 ^216^; RCT-Parallel; n = 168 (Int) and 160 (Comp) | African American: 87%; Latina: 4%; Other: 4%; White: 5%; SES: WIC-eligible families; Location: Baltimore, MD | Int: Breastfeeding support team intervention with hospital visits, home visits, and telephone calls led by community nurse and peer counselor from birth to 24 wk postpartum; Comp: Usual care (inpatient visit by lactation consultant, telephone “warm-line”, up to one office visit with lactation consultant); Analysis adjusted for race and/or ethnicity: Yes | HMF Duration; Any BF, Int vs Comp (ref); At 6 wk: OR (95% CI): 1.72 (1.07, 2.76), p=0.03 | HMF Duration; Any BF at 12 wk, 24 wk
Qureshey, 2020 ^217^; NRCT (Before and After Study); n = 380 (Int) and 337 (Comp) | African American/Black: 12%; Hispanic: 57%; NR: Other races and/or ethnicities; SES: Primarily low-income; Location: Lehigh County, PA | Int: After lactation curriculum for OBGYN residents was instituted; Comp: No lactation curriculum for OBGYN residents (before curriculum was instituted); Analysis adjusted for race and/or ethnicity: No | Exclusive HMF Duration; EBF at 6 wk, Int vs Comp (ref), OR (95% CI) 2.01 (1.28, 3.15) | HMF Initiation; BF Initiation, EBF at hospital discharge
Robertson, 2009 ^218^; NRCT; n = 18 (Int) and 15 (Comp) | Hispanic: 100%; SES: Predominantly had Medicaid or self-paid on sliding scale; Location: GA | Int: Group-based prenatal care (CenteringPregnancy) consisting of 10, 2 h sessions starting at 16-18 wk gestation, and one postpartum ‘reunion’ session. Sessions include self-care skills, basic health information, provider assessments, and group sharing of concerns, support.; Comp: Usual care; Analysis adjusted for race and/or ethnicity: No | | HMF Initiation; Ever BF during first 6 wk; HMF Duration; BF at 6 wk
Rosen-Carole, 2022 ^219^; NRCT (Before and After Study); n = 59-70 (Int) and 62-71 (Comp) | Asian or Pacific or Alaska Native: 4%; Black or African American: 48%; Hispanic or Latina: 16%; Other: 2%; White/Caucasian: 30%; SES: Predominantly low-income; Location: Upstate NY (including Rochester, NY) | Int: Implementation of WIC prenatal BF toolkit with provider recommendations and WIC peer counselor referrals; Comp: Before implementation of WIC BF toolkit; Analysis adjusted for race and/or ethnicity: No | | HMF Initiation; BF Initiation, EBF at hospital; HMF Duration; Any BF at 1 mo; Exclusive HMF Duration; EBF at 1 mo
Schreck, 2017 ^220^; NRCT (Before and After Study); n = 320 (Int) and 330 (Comp) | Black/African American: 84%; Other: 8%; White: 8%; SES: Predominantly low-income; Location: Detroit, MI | Int: Prenatal education on BF by lactation consultants and availability of postnatal BF support group; Comp: Usual care (baseline); Analysis adjusted for race and/or ethnicity: No | HMF Initiation; BF Initiation, Int vs Comp (ref); 71.9% vs 51.5%, p<0.0001 (after controlling for significant demographic and clinical differences, OR=1.7, p=0.027); HMF Duration; BF for at least 6 mo, Int (prenatal edu only) vs Int (prenatal edu + postnatal support group); 59% vs 28%, p=0.002 | HMF Duration; BF duration, Int vs Comp; BF for at least 6 mo, Int vs Comp; Meeting HMF Goals; Meeting BF goals, Int vs Comp
Scott, 2019 ^221^; NRCT; n = 40 (Int) and 40 (Comp) | Marshallese: 100%; SES: NR; Location: Northwest AR | Int: Culturally sensitive, educational video and brochure; Comp: Usual care; Analysis adjusted for race and/or ethnicity: No | | HMF Initiation; EBF during hospitalization
Sebastian, 2019 ^222^; NM PRAMS 2012-2014; Repeated CS; n = 3520 | English-speaking Hispanic: 46%; Native American: 13%; Other: 4%; Spanish-speaking Hispanic: 8%; White, non-Hispanic: 28%; SES: General population; Location: NM | Int: Exposure to BF-friendly maternity care practices (primarily Baby-Friendly Hospital practices); Comp: No exposure to BF-friendly maternity care practices; Analysis adjusted for race and/or ethnicity: No | HMF Duration; Any BF for at Least 2 Months, OR (95% CI); BF at Hospital vs Not; English-speaking Hispanic: 1.99 (1.76, 2.25), p=0.000; Non-Hispanic Native American: 2.71 (2.08, 3.52), p=0.000; Non-Hispanic White: 2.09 (1.67, 2.61), p=0.000; BF within 1st h vs Not; English-speaking Hispanic: 1.18 (1.09, 1.27), p=0.000; Non-Hispanic Native American: 0.42 (0.35, 0.50), p=0.000; Non-Hispanic White: 1.97 (1.75, 2.21), p=0.000; Spanish-Speaking Hispanic: 0.62 (0.48, 0.80), p=0.000; Only BM vs Not; English-speaking Hispanic: 1.96 (1.84, 2.10), p=0.000; Non-Hispanic Native American: 1.40 (1.23, 1.59), p=0.000; Non-Hispanic White: 1.95 (1.76, 2.17), p=0.000; Spanish-Speaking Hispanic: 4.43 (3.56, 5.52), p=0.000; Same Room vs Not; English-speaking Hispanic: 0.75 (0.67, 0.83), p=0.000; Non-Hispanic Native American: 2.43 (1.90, 3.12), p=0.000; Provided Pump vs Not; English-speaking Hispanic: 0.88 (0.82, 0.94), p=0.000; Non-Hispanic White: 1.38 (1.23, 1.54), p=0.000; Spanish-Speaking Hispanic: 0.79 (0.63, 0.99), p=0.036; Provided Information vs Not; English-speaking Hispanic: 0.78 (0.68, 0.90), p=0.001; Non-Hispanic; White: 0.60 (0.49, 0.73), p=0.000; Spanish-Speaking Hispanic: 1.90 (1.26, 2.89), p=0.002; Helped Learn vs Not; English-speaking Hispanic: 0.58 (0.53, 0.63), p=0.000; Non-Hispanic Native American: 0.51 (0.43, 0.61), p=0.000; Non-Hispanic White: 0.76 (0.68, 0.86), p=0.000; Spanish-Speaking Hispanic: 0.37 (0.26, 0.54), p=0.000; On Demand vs Not; English-speaking Hispanic: 1.23 (1.13, 1.34), p=0.000; Non-Hispanic Native American: 1.92 (1.64, 2.25), p=0.000; Non-Hispanic White: 1.40 (1.23, 1.60), p=0.000; Spanish-Speaking Hispanic: 5.18 (3.86, 6.94), p=0.000; Phone Number vs Not; English-speaking Hispanic: 1.26 (1.17, 1.35), p=0.000; Non-Hispanic Native American: 1.78 (1.56, 2.03), p=0.000; Non-Hispanic White: 1.29 (1.15, 1.45), p=0.000; Spanish-Speaking Hispanic: 0.54 (0.43, 0.68), p=0.000; Used Pacifier ([underlined: not] a Baby-Friendly Hospital practice) vs Not; English-speaking Hispanic: 0.73 (0.68, 0.77), p=0.000; Non-Hispanic Native American: 1.44 (1.26, 1.64), p=0.000; Non-Hispanic White: 0.62 (0.56, 0.68), p=0.000; Spanish-Speaking Hispanic: 0.63 (0.52, 0.78), p=0.000; Gave Formula ([underlined: not] a Baby-Friendly Hospital practice) vs Not; English-speaking Hispanic: 0.84 (0.79, 0.90), p=0.000; Non-Hispanic Native American: 0.44 (0.39, 0.50), p=0.000; Non-Hispanic White: 0.65 (0.60, 0.72), p=0.000; Spanish-Speaking Hispanic: 1.81 (1.46, 2.25), p=0.000 | HMF Duration; Any BF for at Least 2 Months: BF at Hospital (Spanish-speaking Hispanic), Same Room (Non-Hispanic White, Spanish-speaking Hispanic), Provided Pump (Non-Hispanic Native American), Provided Information (Non-Hispanic Native American)
Stuebe, 2016 ^223^; Nutrition, Exercise and coping Skills Training (NEST); RCT-Cluster; n = 50 (Int) and 50 (Comp); 85 total provided data on BF | American Indian/Alaskan Native: 9%; Asian: 2%; Black/African American: 52%; More than one race: 4%; Other: 2%; White: 31%; Hispanic: 11%; Not Hispanic: 89%; 100% with gestational diabetes mellitus; SES: Predominantly low-income; Location: Raleigh, NC | Int: Group education and support program on BF, maternal nutrition, exercise, and coping skills delivered prenatally by a lactation consultant (1 class) and postnatally by a trained interventionist (weekly classes and text messages for 13 wk, monthly classes for 3 mo); Comp: Usual care (waitlist control); Analysis adjusted for race and/or ethnicity: Yes | HMF Duration; Any BF over follow-up, Int vs Comp; Int > Comp (Data NR), p<0.01; Any BF at 4 wk, Int vs Comp, % (SE); 87% (5.4%) vs 64% (7.7%), p=NR; BF discontinuation over follow-up, Int vs Comp (ref), HR (95% CI); Overall: 0.40 (0.21, 0.74); Black women: 0.40 (0.20, 0.78) (Note: Int by Race interaction NS); Exclusive HMF Duration; EBF at 4 wk, Int vs Cont, % (SE); 45% (7.9%) vs 23% (6.4%), p=NR | HMF Duration; BF discontinuation over follow-up: White women (Note: Int by Race interaction NS); Exclusive HMF Duration; EBF over follow-up
Watt, 2015 ^224^; NRCT; n = 24 (Int) and 24 (Comp) | Hispanic: 100%; SES: Predominantly low-income; Location: Southwest United States | Int: Primary care, group-based intervention delivered first trimester through 6 mo postpartum and included 4 nutrition education and 6 cooking classes, weekly fruit and vegetable vouchers, and individual lactation counseling (4 sessions); Comp: Usual care (individuals who had indicated interest in the intervention program after enrollment closed); Analysis adjusted for race and/or ethnicity: No | | HMF Duration; BF at 6 mo
Wilhelm, 2015 ^225^; RCT-Parallel; n = 23 (Int) and 27 (Comp) | Mexican-American: 100%; SES: Predominantly low income; Location: Rural areas in western NE, SD, WY, and CO | Int: Motivational interviewing (three, in-home sessions delivered at 3 d, 2 wk, and 6 wk postpartum; aimed at decreasing ambivalence and increasing self-efficacy for BF with the goal of increased BF duration); Comp: Attention control (equal number of visits; content focused on infant safety); Analysis adjusted for race and/or ethnicity: No | | HMF Duration; BF duration at 6 mo

* Abbreviations: %, percent; ~, approximately; AAP, American Academy of Pediatrics; BF, breastfeeding; BM, breast milk; CI, confidence interval; Comp, comparator; CS, cross sectional; d, day; EBF, exclusive breastfeeding; edu, education; h, hour; HM, human milk; HMF, human milk feeding; HR, hazard ratio; IFPS, Infant Feeding Practices Survey; Int, intervention/exposure; ITFPS, Infant and Toddler Feeding Practices Study; min, minute; mo, month; NR, not reported; NRCT, non-randomized controlled trial; NS, non-significant; OR, odds ratio; PCS, prospective cohort study; PRAMS, Pregnancy Risk Assessment Monitoring System; RCS, retrospective cohort study; RCT, randomized controlled trial; ref, reference; SD, standard deviation; SES, socioeconomic status; vs, versus; WIC, Special Supplemental Nutrition Program for Women, Infants, and Children; wk, week; y, year

† The following articles had overlapping study samples: Burnham et al 2022 and Merewood et al 2019

Table 26 Risk of bias for randomized controlled trials examining community-health care system interventions, programs, initiatives, and/or policies and human milk feeding outcomes (Key Question 3)^*^

Article | Randomization | Deviations from intended interventions (effect of assignment) | Missing outcome data | Outcome measurement | Selection of the reported result
Bonuck, 2014^182^ | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS
Chapman, 2013^185^ | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS
Edwards, 2013^187^ | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS
Efrat, 2015^188^ | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS
Gross, 2016^191^ | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS
Hans, 2018^193^ | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS
Hopkinson, 2009^195^ | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS
Howell, 2014^196^ | LOW | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS
Kao, 2015^198^ | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS
Linares, 2019^207^ | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS
Moon, 2017^210^ | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS
Petrova, 2009^214^ | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS
Pugh, 2010^216^ | LOW | LOW | SOME CONCERNS | HIGH | SOME CONCERNS
Wilhelm, 2015^225^ | SOME CONCERNS | LOW | HIGH | HIGH | SOME CONCERNS

* Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2016 version)” (August 2019 version)” ( Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ. 2019:366:l4898. doi: 10.1136/bmj.l4898 31462531 )

Table 27 Risk of bias for cluster randomized controlled trials examining community-health care system interventions, programs, initiatives, and/or policies and human milk feeding outcomes (Key Question 3)^*^

Article | Randomization | Timing of identification and recruitment of individual participants in relation to timing of randomization | Deviations from intended interventions (effect of assignment) | Missing outcome data | Outcome measurement | Selection of the reported result
Stuebe, 2016^223^ | LOW | LOW | LOW | HIGH | SOME CONCERNS | SOME CONCERNS

* Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2016 version)” (August 2019 version)” ( Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ. 2019:366:l4898. doi: 10.1136/bmj.l4898 31462531 )

Table 28 Risk of bias for non-randomized controlled trials and quasi-experimental studies examining community-health care system interventions, programs, initiatives, and/or policies and human milk feeding outcomes (Key Question 3)^*^

Article | Confounding | Selection of participants | Classification of interventions | Deviations from intended interventions | Missing data | Outcome measurement | Selection of the reported result
Ahlers-Schmidt, 2020^179^ | SERIOUS | LOW | LOW | LOW | LOW | LOW | MODERATE
Burnham, 2022^183^ | SERIOUS | MODERATE | MODERATE | LOW | MODERATE | LOW | MODERATE
Chae, 2017^184^ | MODERATE | LOW | LOW | LOW | SERIOUS | MODERATE | MODERATE
Disantis, 2010^186^ | SERIOUS | LOW | LOW | LOW | MODERATE | MODERATE | MODERATE
Ekambaram, 2019^189^ | SERIOUS | LOW | LOW | LOW | SERIOUS | LOW | MODERATE
Grassley, 2012^190^ | SERIOUS | LOW | LOW | LOW | LOW | SERIOUS | MODERATE
Gruber, 2013^192^ | SERIOUS | LOW | LOW | LOW | LOW | NO INFORMATION | MODERATE
Hemingway, 2021^194^ | SERIOUS | LOW | LOW | LOW | LOW | LOW | MODERATE
Keenan-Devlin, 2021^199^ | MODERATE | LOW | LOW | LOW | MODERATE | LOW | MODERATE
Kelly, 2017^200^ | SERIOUS | LOW | LOW | LOW | LOW | MODERATE | MODERATE
Kettrey, 2020^201^ | MODERATE | LOW | LOW | LOW | MODERATE | LOW | MODERATE
Klima, 2009^202^ | SERIOUS | LOW | MODERATE | LOW | LOW | LOW | MODERATE
Knutson, 2022^203^ | SERIOUS | LOW | MODERATE | LOW | NO INFORMATION | LOW | SERIOUS
Kozhimannil, 2013^204^ | SERIOUS | MODERATE | LOW | LOW | NO INFORMATION | SERIOUS | MODERATE
Lau, 2021^206^ | SERIOUS | LOW | LOW | LOW | LOW | LOW | MODERATE
Martinez, 2020^208^ | MODERATE | LOW | LOW | LOW | LOW | MODERATE | MODERATE
Merewood, 2019^209^ | SERIOUS | LOW | LOW | LOW | LOW | LOW | MODERATE
Nommsen-Rivers, 2009^212^ | SERIOUS | LOW | LOW | LOW | SERIOUS | MODERATE | MODERATE
Patberg, 2021^213^ | SERIOUS | LOW | LOW | LOW | NO INFORMATION | LOW | MODERATE
Pitcock, 2021^215^ | SERIOUS | LOW | LOW | LOW | LOW | LOW | MODERATE
Qureshey, 2020^217^ | MODERATE | LOW | LOW | LOW | LOW | LOW | MODERATE
Robertson, 2009^218^ | SERIOUS | LOW | LOW | LOW | SERIOUS | MODERATE | MODERATE
Rosen-Carole, 2022^219^ | MODERATE | LOW | LOW | LOW | MODERATE | SERIOUS | MODERATE
Schreck, 2017^220^ | SERIOUS | LOW | LOW | LOW | SERIOUS | MODERATE | MODERATE
Scott, 2019^221^ | SERIOUS | LOW | LOW | LOW | LOW | LOW | MODERATE
Watt, 2015^224^ | SERIOUS | LOW | LOW | LOW | MODERATE | MODERATE | MODERATE

* Possible ratings of low, moderate, serious, critical, or no information determined using the “Risk of Bias in Non-randomized Studies of Interventions (ROBINS-I) tool” (https://www.riskofbias.info/welcome/home/current-version-of-robins-i) ( Sterne JAC, Hernán MA, Reeves BC, Savović J, Berkman ND, Viswanathan M, Henry D, Altman DG, Ansari MT, Boutron I, Carpenter JR, Chan AW, Churchill R, Deeks JJ, Hróbjartsson A, Kirkham J, Jüni P, Loke YK, Pigott TD, Ramsay CR, Regidor D, Rothstein HR, Sandhu L, Santaguida PL, Schünemann HJ, Shea B, Shrier I, Tugwell P, Turner L, Valentine JC, Waddington H, Waters E, Wells GA, Whiting PF, Higgins JPT. ROBINS-I: a tool for assessing risk of bias in non-randomized studies of interventions. BMJ 2016; 355; i4919; doi: 10.1136/bmj.i4919.27733354 )

Table 29 Risk of bias for observational studies examining community-health care system interventions, programs, initiatives, and/or policies and human milk feeding outcomes (Key Question 3)^*^

Article | Confounding | Selection of participants | Classification of exposures | Deviations from intended exposures | Missing data | Outcome measurement | Selection of the reported result
Ahluwalia, 2012^180^ | MODERATE | LOW | LOW | LOW | MODERATE | MODERATE | MODERATE
Beauregard, 2022^181^ | SERIOUS | LOW | MODERATE | LOW | MODERATE | MODERATE | MODERATE
Jung, 2019^197^ | SERIOUS | LOW | MODERATE | LOW | LOW | MODERATE | MODERATE
Langellier, 2012^205^ | SERIOUS | LOW | MODERATE | LOW | NO INFORMATION | MODERATE | MODERATE
Nobari, 2017^211^ | SERIOUS | LOW | LOW | LOW | NO INFORMATION | MODERATE | MODERATE
Sebastian, 2019^222^ | SERIOUS | LOW | MODERATE | LOW | LOW | MODERATE | MODERATE

* Possible ratings of low, moderate, serious, critical, or no information determined using the “Risk of Bias for Nutrition Observational Studies” tool (RoB-NObs) ( Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC. )

### NIMHD framework: societal level – behavioral domain

#### Description of the evidence

This rapid review includes nine articles (from eight studies) that were categorized as examining societal-behavioral interventions, programs, initiatives, or policies.^178,226–233^ The characteristics and results of each individual article are described in Table 30.

All of the studies used a repeated cross-sectional design, with most assessing human milk feeding outcomes before and after implementation of a variety of state or national level policies and laws. Data sources for these studies included the Los Angeles County WIC Survey,^229^ the NHANES,^231,232^ the New York State WIC Statewide Information System,^178^ the PRAMS 2000-2008 (31 States)^228^ and 2016-2019 (New York),^226^ and WIC administrative records,^233^ in addition to one unnamed data source.^230^ Sample sizes ranged from 196^230^ to 3,562,184^178^ total participants.

Five of the studies were conducted with U.S. national samples or across multiple States,^227,228,231–233^ with the remaining studies conducted in Los Angeles County, CA,^229^ New York,^178,226^ and South-Central Texas.^230^ Regarding SES, five of the studies were conducted within the general population,^226–228,231,232^ whereas four studies were conducted exclusively with individuals participating in WIC.^178,229,230,233^ All articles included participants from several racial and/or ethnic groups, although the proportions varied across studies, including two articles that predominantly included participants who were Hispanic or Latina.^229,230^ The studies primarily described participants as women or mothers; this terminology is used throughout this section, as appropriate.

The policies and laws assessed across the articles included the 2009 revision of the WIC food packages (four studies),^178,229,230,233^ State paid family leave laws (two studies),^226,227^ and State laws pertaining to human milk feeding (two studies).^228,231,232^

All nine articles assessed human milk feeding initiation, seven examined human milk feeding duration,^226–232^ and two examined exclusive human milk feeding duration.^227,229^ None of the articles reported on the outcome of meeting human milk feeding goals.

#### Evidence synthesis

Eight repeated cross-sectional studies examined societal-behavioral interventions, programs, initiatives, or policies,^178,226–233^ six of which detected significant impacts on human milk feeding initiation (six of eight studies),^178,226–233^ human milk feeding duration (four of six studies),^226–232^ and/or exclusive human milk feeding duration (two of two studies).^227,229^

For each of the three broad categories of policies and laws that were assessed, positive impacts on human milk feeding outcomes were reported. However, there were notable areas of inconsistency and variability within and across studies, and the number of studies for each category of policy or law was low. For studies examining the 2009 WIC food package revision, two of four reported positive impacts on human milk feeding initiation,^178,229,230,233^ neither of the two studies that assessed human milk feeding duration reported positive impacts,^229,230^ and the one study that assessed exclusive human milk feeding duration reported positive impacts.^229^ Among studies that examined paid family leave laws, positive impacts were reported for human milk feeding initiation (one of two studies),^226,227^ human milk feeding duration (one of two studies),^226,227^ and exclusive human milk feeding duration (one of one study).^227^ The impact that these laws had on human milk feeding outcomes varied across racial and/or ethnic groups, but was not consistent between studies.^226,227^ Finally, among studies that examined laws supporting breastfeeding, positive impacts were reported for both human milk feeding initiation (two of two studies) and human milk feeding duration (two of two studies).^228,231,232^ The impact that these laws had on human milk feeding outcomes appeared to vary across racial and/or ethnic groups, with more consistent benefits reported for Hispanic women.^228,231,232^

The evidence was assessed using the following domains:

- [underlined: Consistency]: There were areas of consistency and inconsistency across the included articles. Looking across all studies, most reported positive impacts of the policies or laws assessed on one or more human milk feeding outcomes. However, the results of studies on the WIC food package revision were mixed, with one study reporting positive impacts of the revision alone on human milk feeding outcomes,^229^ one reporting positive impacts of the revision in a population simultaneously introduced to the New York State WIC Healthy Lifestyle Initiative, which included breastfeeding peer counseling and client-centered counseling,^178^ and two reporting no significant associations.^230,233^ Studies examining the impact of paid family leave reported contrasting results by racial and/or ethnic group. Specifically, Non-Hispanic Black women showed particular benefit in one study (with no significant associations among other racial and/or ethnic groups),^226^ while a second study found that Non-Hispanic Black women were impacted less favorably and Hispanic women were impacted more favorably by paid family leave than White women.^227^ Finally, consistency between the two studies on State laws related to breastfeeding appeared to vary by race and/or ethnicity. In both studies, laws that provided break time for breastfeeding at work had significant positive impacts on human milk feeding outcomes for Hispanic or Mexican American women relative to White women.^228,232^ In contrast, while one study showed benefits of laws permitting breastfeeding in any public or private location for Black women relative to White women,^228^ the second study did not show significant impacts of this category of law relative to White women, and several laws had a significantly lower impacts in Black women compared to White women.^232^
- [underlined: Precision]: Sample size varied across the included articles, ranging from small (under 200 participants) to very large (over 3.5 million participants). However, most studies included several thousand or more participants. The confidence intervals for significant results were relatively small.
- [underlined: Risk of bias]: There were several risk of bias domains that were of concern across the studies (see Table 31 and Table 32). Specifically, most studies were assessed as having serious risk of bias due to confounding, and moderate risk of bias due to outcome measurement and selection of reported result. Approximately half of the studies were assessed as having either moderate or serious risk of bias due to missing data.
- [underlined: Directness]: The studies aligned with the population, intervention/exposure, comparator, and outcome in the analytic framework.
- [underlined: Generalizability]: The studies were largely generalizable to the populations of interest for the review. Several studies used data from national samples, while others used data from State- or County-wide datasets. Some studies analyzed data by race and ethnicity, however not all studies took this approach. In particular, all four studies that assessed the 2009 WIC food package did not conduct analyses by race or ethnicity, limiting the ability to assess the potential for differing or similar impacts among individuals from different racial and/or ethnic groups.

#### Summary statement

Evidence suggests that societal-behavioral policies, including paid family leave laws and laws supporting human milk feeding, may be associated with more favorable human milk feeding outcomes in populations predominantly consisting of individuals from U.S. racial and ethnic minority groups. However, the policies and laws assessed across all the studies were heterogenous, the number of studies available for each category of policy or law was relatively small, and there was some inconsistency in results by racial and/or ethnic group. The evidence was further limited by several risk of bias concerns.

Table 30 Evidence for societal-behavioral interventions, programs, initiatives, and/or policies and human milk feeding outcomes (Key Question 3)^*^,^†^

Study | Study Participants | Intervention and Comparator; Adjustment for Race and/or Ethnicity | Significant Results | Non-Significant Results
Chiasson, 2013 ^178^; NYS WIC Statewide Information System; Repeated CS (Before and After Study); n = 3,067,873 (Int, 01/2009-12/2011) and 494,311 (Comp, 07/2008-12/2008) | Asian: ~8%; Black Non-Hispanic: ~24%; Hispanic: ~38%; Other: ~2%; White Non-Hispanic: ~28%; SES: WIC participants; Location: NY | Int: Implementation of revised WIC food package and NYS WIC Healthy Lifestyle Initiative (BF peer counseling and client-centered counseling); Comp: Pre-implementation of revised WIC food package and NYS WIC Healthy Lifestyle Initiative; Analysis adjusted for race and/or ethnicity: No | HMF Initiation; BF Initiation; Comp (07/2008-12/2008): 72.2%; Int (01/2009-06/2009): 73.0%; Int (07/2009-12/2009): 73.9%; Int (01/2010-06/2010): 74.8%; Int (07/2010-12/2010): 75.7%; Int (01/2011-06/2011): 76.6%; Int (07/2011-12/2011): 77.5%; Relative % Change (2008-2011): 7.3%; (Note - statistical significance tests not conducted because data represents census of all WIC-participating children in NYS)
Dennison, 2022 ^226^; NY PRAMS 2016-2019; Repeated CS (Before and After Study); n = 879 (Int) and 797 (Comp) | Hispanic: ~11%; Non-Hispanic Black: ~10%; Non-Hispanic Other: ~7%; Non-Hispanic White: ~72%; SES: General population; Location: NY (Excluding NYC) | Int: Post-implementation of NY’s Paid Family Leave law; Comp: Pre-implementation of NY’s Paid Family Leave Law; Analysis adjusted for race and/or ethnicity: NR | HMF Initiation; BF Initiation, Int vs Comp; Non-Hispanic Black: 96.5% vs 76.2%, p=0.0004; Non-Hispanic Other: 99.7% vs 92.3%, p<0.001; BF Initiation, Int vs Comp (ref), Prevalence Ratio (95% CI); Non-Hispanic Black: 1.27 (1.02, 1.56); HMF Duration; BF to 4 wk, Int vs Comp; Non-Hispanic Black: 86.0% vs 62.2%, p=0.01; BF to 4 wk, Int vs Comp (ref), Prevalence Ratio (95% CI); Non-Hispanic Black: 1.38 (1.02, 1.87); BF to 8 wk, Int vs Comp; Non-Hispanic Black: 79.0% vs 43.6%, p=0.002; BF to 8 wk, Int vs Comp (ref), Prevalence Ratio (95% CI); Non-Hispanic Black: 1.81 (1.19, 2.75) | HMF Initiation; BF Initiation: Overall, Hispanic, Non-Hispanic White; HMF Duration; BF to 4 wk, 8 wk: Overall, Hispanic, Non-Hispanic Other, Non-Hispanic White; BF to 10 wk, 12 wk: Overall, Hispanic, Non-Hispanic Black, Non-Hispanic Other, Non-Hispanic White
Hamad, 2019 ^227^; NIS 2003-2015; Repeated CS (Before and After Study); n = 306,266 | Black; Hispanic; Other; White; (% NR); SES: General population; Location: U.S. National Sample | Int: State paid family leave policy (6 wk of partially paid leave) (CA, NJ; pre-post implementation change); Comp: No state paid family leave policy (pre-post implementation change); Analysis adjusted for race and/or ethnicity: Yes | HMF Initiation; Ever BF, Int vs Comp (ref); Other vs White (ref): Diff in change (95% CI): −2.6% points (−5.1, −0.1), p<0.05; HMF Duration; BF at 6 mo, Int vs Comp (ref); Black vs White (ref): Diff in change (95% CI): −3.8% points (−7.3, −0.3), p<0.05; BF at 12 mo, Int vs Comp (ref); Black vs White (ref): Diff in change (95% CI): −2.9% points (−4.8, −1.0), p<0.01; BF duration, Int vs Comp (ref); Black vs White (ref): Mean diff in change (95% CI): −15.5 days (−24.2, −6.9), p<0.001; Exclusive HMF Duration; EBF at 6 mo, Int vs Comp (ref); Overall: 1.3% points (0.6, 2.0); Hispanic vs White (ref): Diff in change (95% CI): 2.3% points (1.2, 3.4), p<0.001 | HMF Initiation; Ever BF: Overall, Black vs White, Hispanic vs White; HMF Duration; BF at 6 mo and 12 mo: Overall, Hispanic vs White, Other vs White; BF duration: Overall, Hispanic vs White, Other vs White; Exclusive HMF Duration; EBF at 3 mo: Overall, Black vs White, Hispanic vs White, Other vs White; EBF at 6 mo: Black vs White, Other vs White; EBF duration: Overall, Black vs White, Hispanic vs White, Other vs White
Hawkins, 2013 ^228^; PRAMS 2000-2008; Repeated CS (Before and After Study); n = 319,431 - 326,260 | Black; Hispanic; Other; White; (% NR); SES: General population; Location: 31 States (AL, AK, AR, CO, DE, FL, GA, HI, IL, LA, MA, MD, ME, MI, MN, MS, NC, NE, NJ, NM, NY (including NYC), OH, OK, OR, RI, SC, UT, WA, WI, WV, WY) | Int: Implementation of laws in which employers are encouraged or required to provide break time and private space for BF employees; Int 2: Implementation of laws in which BF is permitted in any public or private location; Comp: No law pertaining to encouraging/requiring break time/private space and/or to permitting BF in any public or private location; Analysis adjusted for race and/or ethnicity: Yes | HMF Initiation; BF Initiation, Beta coefficient (95% CI); Int (laws for break time/private space) vs Comp (Not; ref); Overall: 0.017 (0.00, 0.03); Hispanic vs White (ref): 0.048 (0.01, 0.09); Int 2 (laws for any public/private location) vs Comp (Not; ref); Black vs White (ref): 0.060 (0.01, 0.11); HMF Duration; BF for at least 4 wk, Beta coefficient (95% CI); Int (laws for break time/private space) vs Comp (Not; ref); Hispanic vs White (ref): 0.062 (0.01, 0.12); Int 2 (laws for any public/private location) vs Comp (Not; ref); Black vs White (ref): 0.056 (0.02, 0.10) | HMF Initiation; BF Initiation: Int (laws for break time/private space) for Black vs White, Other vs White; Int 2 (laws for any public/private location) for Overall, Hispanic vs White, Other vs White; HMF Duration; BF for at least 4 wk: Int (laws for break time/private space) for Overall, Black vs White, Other vs White; Int 2 (laws for any public/private location) for Overall, Hispanic vs White, Other vs White
Langellier, 2014 ^229^; Los Angeles County WIC Survey 2005/2008/2011; Repeated CS (Before and After Study); n = 3,428 - 5,020 | Asian: ~2%; Black: ~7%; Latina: ~84%; Other or Multiple: ~2%; White: ~5%; SES: WIC participants; Location: Los Angeles County, CA | Int: Post-implementation of revised WIC food package (2011); Comp: Pre-implementation of revised WIC food package (2005, 2008); Analysis adjusted for race and/or ethnicity: Yes | HMF Initiation; Ever BF, Int vs Comp (ref), OR (95% CI) 2.16 (1.69, 2.76), p<0.001; Exclusive HMF Duration; EBF, Int vs Comp (ref), OR (95% CI); At 3 mo: 1.72 (1.43, 2.07), p<0.001; At 6 mo: 3.08 (2.27, 4.18), p<0.001 | HMF Duration; Any BF at 3 mo and 6 mo
Reat, 2015 ^230^; Repeated CS (Before and After Study); n = 112 (Int) and 84 (Comp) | Hispanic: ~65%; Non-Hispanic White: ~17%; Other: ~18%; SES: WIC participants; Location: South Central TX | Int: Post-implementation of revised WIC food package (2011); Comp: Pre-implementation of revised WIC food package (2009); Analysis adjusted for race and/or ethnicity: No | | HMF Initiation; Initiated BF; HMF Duration; BF duration (continuous, ≥3 mo, ≥6 mo, ≥12 mo)
Smith-Gagen, 2014a ^231^; NHANES 2003-2010; Repeated CS; n = 2,843 - 3,207 | Black: 19%; Mexican: 34%; Other: 14%; White: 32%; SES: General population; Location: U.S. National Sample | Int: Exposure to State law related to BF; Comp: No exposure to State law related to BF; Analysis adjusted for race and/or ethnicity: Yes | HMF Initiation; Ever BF, OR (95% CI); BF in any public location vs Not (ref): 1.43 (1.1, 1.9), p=0.01; Workplace private area to pump vs Not (ref): 1.43 (1.1, 1.9), p=0.02; Jury duty exemption vs Not (ref): 1.81 (1.2, 2.8), p=0.01; Pumping enforcement vs Not (ref): 3.25 (2.3, 4.7), p<0.0001; HMF Duration; BF at Least 6 mo, OR (95% CI); Workplace private area to pump vs Not (ref): 1.34 (1.1, 1.7), p=0.01; Jury duty exemption vs Not (ref): 1.66 (1.3, 2.1), p<0.0001; Pumping enforcement vs Not (ref): 2.02 (1.6, 2.6), p<0.0001 | HMF Initiation; Ever BF:; Exempt from indecency laws; Workplace break time to BF; BF awareness education campaign; BF in public enforcement; HMF Duration; BF at Least 6 mo:; BF in any public location; Exempt from indecency laws; Workplace break time to BF; BF awareness education campaign; BF in public enforcement
Smithr-Gagen, 2014b ^232^; NHANES 2003-2010; Repeated CS; n = 3,132 | African American: 23%; Mexican American: 40%; White: 37%; SES: General population; Location: U.S. National Sample | Int: Exposure to a variety of State laws related to BF; Comp: No exposure to a variety of State laws related to BF; Analysis adjusted for race and/or ethnicity: No | HMF Duration; BF for 6 mo or More, OR (95% CI); Break-time from work vs Not (ref); African American vs White (ref): 0.6 (0.5, 0.8), p<0.05; Mexican American vs White (ref): 1.3 (1.0, 1.8), p<0.05; Private area to pump at work vs Not (ref); African American vs White (ref): 0.6 (0.4, 0.8), p<0.05; Exempt from jury duty vs Not (ref); African American vs White (ref): 0.6 (0.4, 0.9), p<0.05; Awareness education campaign vs Not (ref); African American vs White (ref):0.5 (0.3, 0.8), p<0.05; Pumping law enforcement vs Not (ref); African American vs White (ref): 0.6 (0.5, 0.8), p<0.05; Mexican American vs White (ref): 1.2 (1.0, 1.5), p<0.05 | HMF Initiation; Ever BF (All comparisons - African American vs White, Mexican American vs White):; Exempt from indecency laws; BF in any public or private location; Break-time from work; Private area to pump at work; Exempt from jury duty; Awareness education campaign; Pumping law enforcement; Public BF law enforcement; HMF Duration; BF for 6 mo or More:; Exempt from indecency laws (African American vs White, Mexican American vs White); BF in any public or private location (African American vs White, Mexican American vs White); Private area to pump at work (Mexican American vs White); Exempt from jury duty (Mexican American vs White); Awareness education campaign (Mexican American vs White); Public BF law enforcement (African American vs White, Mexican American vs White)
Wilde, 2012 ^233^; WIC Administrative Records; Repeated CS (Before and After Study); n = 77,534 (Int) and 80,658 (Comp) | Hispanic: ~50%; Non-Hispanic Black: ~23%; White: ~10%; SES: WIC participants; Location: Ten States (CA, FL, GA, ID, IL, MN, RI, TN, TX, UT) | Int: 1-8 mo post-implementation of revised WIC food package; Comp: 2-3 mo pre-implementation of revised WIC food package; Analysis adjusted for race and/or ethnicity: Yes | | HMF Initiation; BF Initiation

* Abbreviations: %, percent; ~, approximately; BF, breastfeeding; CI, confidence interval; Comp, comparator; CS, cross sectional; diff, difference; EBF, exclusive breastfeeding; HMF, human milk feeding; Int, intervention/exposure; mo, month; NHANES, National Health and Nutrition Examination Survey; NIS, National Immunization Survey; OR, odds ratio; PRAMS, Pregnancy Risk Assessment Monitoring System; ref, reference; SE, standard error; SES, socioeconomic status; vs, versus; WIC, Special Supplemental Nutrition Program for Women, Infants, and Children; wk, week

† The following articles are from the same study or had overlapping study samples: Smith-Gagen et al 2014a and Smith-Gagen et al 2014b

Table 31 Risk of bias for non-randomized controlled trials and quasi-experimental studies examining societal-behavioral interventions, programs, initiatives, and/or policies and human milk feeding outcomes (Key Question 3)^*^

Article | Confounding | Selection of participants | Classification of interventions | Deviations from intended interventions | Missing data | Outcome measurement | Selection of the reported result
Chiasson, 2013^178^ | SERIOUS | LOW | MODERATE | LOW | LOW | MODERATE | MODERATE
Dennison, 2022^226^ | SERIOUS | LOW | LOW | LOW | LOW | MODERATE | MODERATE
Hamad, 2019^227^ | SERIOUS | LOW | LOW | LOW | LOW | MODERATE | MODERATE
Hawkins, 2013^228^ | MODERATE | LOW | LOW | LOW | MODERATE | MODERATE | MODERATE
Langellier, 2014^229^ | SERIOUS | LOW | LOW | LOW | MODERATE | MODERATE | MODERATE
Reat, 2015^230^ | SERIOUS | LOW | LOW | LOW | SERIOUS | MODERATE | MODERATE
Wilde, 2012^233^ | SERIOUS | LOW | LOW | LOW | LOW | MODERATE | MODERATE

* Possible ratings of low, moderate, serious, critical, or no information determined using the “Risk of Bias in Non-randomized Studies of Interventions (ROBINS-I) tool” (https://www.riskofbias.info/welcome/home/current-version-of-robins-i) ( Sterne JAC, Hernán MA, Reeves BC, Savović J, Berkman ND, Viswanathan M, Henry D, Altman DG, Ansari MT, Boutron I, Carpenter JR, Chan AW, Churchill R, Deeks JJ, Hróbjartsson A, Kirkham J, Jüni P, Loke YK, Pigott TD, Ramsay CR, Regidor D, Rothstein HR, Sandhu L, Santaguida PL, Schünemann HJ, Shea B, Shrier I, Tugwell P, Turner L, Valentine JC, Waddington H, Waters E, Wells GA, Whiting PF, Higgins JPT. ROBINS-I: a tool for assessing risk of bias in non-randomized studies of interventions. BMJ 2016; 355; i4919; doi: 10.1136/bmj.i4919.27733354 )

Table 32 Risk of bias for observational studies examining societal-behavioral interventions, programs, initiatives, and/or policies and human milk feeding outcomes (Key Question 3)^*^

Article | Confounding | Selection of participants | Classification of exposures | Deviations from intended exposures | Missing data | Outcome measurement | Selection of the reported result
Smith-Gagen, 2014a^231^ | SERIOUS | LOW | LOW | LOW | MODERATE | MODERATE | MODERATE
Smith-Gagen, 2014b^232^ | SERIOUS | LOW | LOW | LOW | LOW | MODERATE | MODERATE

* Possible ratings of low, moderate, serious, critical, or no information determined using the “Risk of Bias for Nutrition Observational Studies” tool (RoB-NObs) ( Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC. )

### NIMHD framework: societal level – health care system domain

#### Description of the evidence

This rapid review includes one article that examined a societal-health care system intervention, program, initiative, or policy.^234^ The characteristics and results of this study are presented in Table 33. This study used a repeated cross-sectional design to assess the impact of the Affordable Care Act (ACA), which mandated lactation support services, on human milk feeding initiation. Human milk feeding duration, exclusive human milk feeding duration, and meeting human milk feeding goals were not examined. This article utilized data from the National Vital Statistics System (NVSS), which compiles data from all birth certificates across the United States, including 17,985,584 participants. This study primarily described participants as mothers; this terminology is used throughout this section, as appropriate.

#### Evidence synthesis

Only one study was identified that examined a societal-health care system intervention, program, initiative, or policy, finding that ACA-mandated lactation support services were associated with higher rates of breastfeeding initiation for American Indian/Alaska Native, Black/African American, and White mothers, while no association was detected for Asian/Pacific Islander mothers.^234^ The evidence was assessed using the following domains:

- [underlined: Consistency]: Because only one study was categorized as a societal-health care intervention, program, initiative, and/or policy, consistency cannot be assessed.
- [underlined: Precision]: This study included nearly 18 million participants with small, but meaningful, effect sizes for several racial and/or ethnic groups (e.g., Black/African American). However, for some racial and/or ethnic groups (e.g., American Indian/Alaska Native) the standard errors of the effect estimates were relatively large.
- [underlined: Risk of bias]: There were some concerns regarding risk of bias (see Table 34). Specifically, bias due to confounding and bias in selection of participants were both assessed as moderate, while bias due to missing data was not assigned a rating due to a lack of information. The remaining risk of bias domains were assessed as low (selection of participants into study, classification of interventions, deviations from intended interventions, measurement of outcomes).
- [underlined: Directness]: This study aligned with the population, intervention/exposure, comparator, and outcome in the analytic framework.
- [underlined: Generalizability]: This study is likely generalizable to U.S. populations of interest based on its inclusion of mothers of varying socio-demographic characteristics, including SES and several racial and/or ethnic groups. However, no analyses were run to estimate impacts in Hispanic mothers due to differences in how Hispanic ethnicity was collected across State birth certificates during the study period.

#### Summary statement

There is not enough evidence to develop a summary statement for societal-health care system interventions, programs, initiatives, and policies.

Table 33 Evidence for societal-health care system interventions, programs, initiatives, and/or policies and human milk feeding outcomes (Key Question 3)^*^

Study | Study Participants | Intervention and Comparator; Adjustment for Race and/or Ethnicity | Significant Results | Non-Significant Results
Kapinos, 2017 ^234^; NVSS 2009-2014; Repeated CS (Before and After Study); n = 17,985,584 | American Indian/Alaska Native: 1%; Asian/Pacific Islander: 6%; Black: 16%; White: 77%; Hispanic: 33%; SES: General population; Location: United States | Int: ACA-mandated lactation support services (2013 or 2014) – private insurance vs Medicaid; Comp: Prior to mandate (2009) – private insurance vs Medicaid; Analysis adjusted for race and/or ethnicity: Yes | HMF Initiation; BF Initiation, Int (2013) vs Comp (2009) (ref), Difference-in-differences (SE); American Indian/Alaska Native: 0.021 (0.01), p<0.05; Black/African American: 0.032 (0.0002), p<0.01; White: 0.009 (0.001), p<0.01; Black/African American > White, p<0.05; BF Initiation, Int (2014) vs Comp (2009) (ref), Difference-in-differences (SE); American Indian/Alaska Native: 0.039 (0.01), p<0.01; Black/African American: 0.034 (0.002), p<0.01; White: 0.025 (0.001), p<0.01; Asian/Pacific Islander (−0.005 (0.004)) < White), p<0.05; Black/African American vs White, p<0.05 | HMF Initiation; BF Initiation, 2013 vs 2009: Asian/Pacific Islander; American Indian/Alaska Native vs White; Asian/Pacific Islander vs White; BF Initiation, 2014 vs 2009: Asian/Pacific Islander; American Indian/Alaska Native vs White

* Abbreviations: %, percent; ACA, Affordable Care Act; BF, breastfeeding; Comp, comparator; CS, cross sectional; HMF, human milk feeding; Int, intervention/exposure; NVSS, National Vital Statistics System; ref, reference; SE, standard error; SES, socioeconomic status; vs, versus

Table 34 Risk of bias for non-randomized controlled trials and quasi-experimental studies examining societal-health care system interventions, programs, initiatives, and/or policies and human milk feeding outcomes (Key Question 3)^*^

Article | Confounding | Selection of participants | Classification of interventions | Deviations from intended interventions | Missing data | Outcome measurement | Selection of the reported result
Kapinos, 2017^234^ | MODERATE | LOW | LOW | LOW | NO INFORMATION | LOW | MODERATE

* Possible ratings of low, moderate, serious, critical, or no information determined using the “Risk of Bias in Non-randomized Studies of Interventions (ROBINS-I) tool” (https://www.riskofbias.info/welcome/home/current-version-of-robins-i) ( Sterne JAC, Hernán MA, Reeves BC, Savović J, Berkman ND, Viswanathan M, Henry D, Altman DG, Ansari MT, Boutron I, Carpenter JR, Chan AW, Churchill R, Deeks JJ, Hróbjartsson A, Kirkham J, Jüni P, Loke YK, Pigott TD, Ramsay CR, Regidor D, Rothstein HR, Sandhu L, Santaguida PL, Schünemann HJ, Shea B, Shrier I, Tugwell P, Turner L, Valentine JC, Waddington H, Waters E, Wells GA, Whiting PF, Higgins JPT. ROBINS-I: a tool for assessing risk of bias in non-randomized studies of interventions. BMJ 2016; 355; i4919; doi: 10.1136/bmj.i4919.27733354 )