# Chapter 3 What factors are associated with racial and/or ethnic disparities in human milk feeding in the United States? (Key Question 2)

## Plain-language summary

#### What is the question?

What factors are associated with racial and/or ethnic disparities in human milk feeding in the United States?

#### Why was this question asked?

To summarize evidence on factors associated with racial and ethnic disparities in human milk feeding, in order to inform Food and Nutrition Service (FNS) communication and program guidance on these topics.

#### How was this question answered?

The Nutrition Evidence Systematic Review (NESR) team conducted a rapid review to answer this question.

#### What was the population of interest?

The population of interest is parent-infant dyads living in the United States.

#### How up-to-date is this rapid review?

This review searched for studies published between January 2009 and June 2022.

#### What evidence was found and what is the answer to the question?

The factors examined in the articles were organized based on the National Institute on Minority Health and Health Disparities (NIMHD) research framework. The following factors were narratively identified in qualitative studies or were assessed as mediators or moderators in the relationship between race and/or ethnicity and human milk feeding in quantitative studies:

##### Quantitative data

This rapid review identified 55 quantitative factors from 71 included articles. However, 13 factors had enough evidence in a consistent direction to draw summary statements and are described below.

The following factors may be associated with the relationship between race and ethnicity and human milk feeding outcomes:

###### NIMHD framework: individual level – biological domain

- Pre-pregnancy obesity (initiation only): Evidence suggests that pre-pregnancy obesity, compared to a normal pre-pregnancy BMI, may be associated with lower human milk feeding initiation among White, but not Black, mothers. (5 studies)

###### NIMHD framework: individual level – sociocultural environment domain

- Maternal nativity (initiation only): Evidence suggests that maternal nativity may be associated with the relationship between race and human milk feeding initiation among Black and White mothers, such that foreign-born Black mothers initiated human milk feeding at higher rates than U.S.-born Black mothers, while associations were inconsistent for White mothers. (6 studies)
- Maternal education (duration only): Evidence suggests that lower levels of maternal education may be associated with shorter human milk feeding duration for Black mothers compared to White mothers. (5 studies)

The following factors may not be associated with the relationship between race and ethnicity (Black, Hispanic, and White mothers unless otherwise noted) and human milk feeding outcomes: gestational age (initiation only, 5 studies), postpartum depression (duration only, 4 studies), smoking (initiation, 8 studies and duration, 4 studies), maternal age (initiation, 6 studies and duration, 4 studies), maternal education (initiation only, 11 studies), income and income-related factors (initiation only, 7 studies), parity (initiation, 7 studies and duration, 4 studies), employment or aspects of employment (Black, White, and Other mothers, initiation only, 3 studies from 4 articles), marital status (Black, White, Hispanic, and Other mothers, initiation only, 10 studies), WIC participation (duration only, 7 studies), and baby-friendly hospital practices (initiation only, 4 studies).

##### Qualitative data

This rapid review identified 45 qualitative themes from 72 included articles related to the relationship between race and ethnicity and human milk feeding. Themes were categorized as having either a positive or negative relation to human milk feeding outcomes.

###### NIMHD framework: Individual level – biological domain

- Physical breastfeeding problems (39 studies: all negative themes)
- Health issues (10 studies: 2 positive, 9 negative themes)

###### NIMHD framework: Individual level – behavioral domain

- Breastfeeding beliefs, knowledge, and experiences: breastfeeding attitudes (14 studies: 7 positive, 10 negative themes); breastfeeding being convenient or easy (9 studies: 8 positive, 2 negative themes); breast milk is nutritionally unreliable or insufficient (13 studies: all negative themes); body image (8 studies: all negative themes); cost (10 studies: 9 positive, 3 negative themes); fear (8 studies: all negative themes); health benefits (42 studies [43 articles], 42 positive, 1 negative themes); infant attachment (7 studies: all negative themes); knowledge (12 studies: 7 positive, 8 negative themes); life demands and stress (8 studies: all negative themes); lifestyle (10 studies: 1 positive, 9 negative themes); not knowing if infant was adequately fed (7 studies: all negative themes); infant age (2 studies: all negative themes); time and responsibilities (22 studies: 1 positive, 22 negative themes)
- Formula feeding beliefs: attitudes (4 studies: 3 positive, 3 negative themes); convenience and ease of formula feeding (13 studies: 1 positive, 12 negative themes); health benefits of formula feeding (6 studies: all negative themes)
- Confidence (15 studies: 10 positive, 10 negative themes)
- Intention to breastfeed or formula feed (6 studies: 6 positive, 2 negative themes)
- Introduction to solid foods (2 studies: all negative themes)
- Perseverance (23 studies: 22 positive, 5 negative themes)
- Previous breastfeeding experience (10 studies: 10 positive, 1 negative themes)

###### NIMHD framework: Individual level – health care system domain

- Cost of hospital lactation services (1 study: 1 negative theme)

###### NIMHD framework: Interpersonal level – behavioral domain

- Infant preferences (8 studies: 1 positive, 7 negative themes)
- Sharing care of the infant (12 studies: all negative themes)

###### NIMHD framework: Interpersonal level – physical/built environment domain

- Home environment (3 studies: 1 positive, 3 negative themes)
- Returning to work (30 studies: 2 positive, 28 negative themes)
- Work environment (23 studies: 10 positive, 19 negative themes)

###### NIMHD framework: Interpersonal level – sociocultural environment domain

- Exposure to breastfeeding (23 studies: 18 positive, 13 negative themes)
- Exposure to formula feeding (6 studies: all negative themes)
- Sexualized view of breasts and breastfeeding (7 studies: all negative themes)
- Social support: social support from partner (27 studies: 21 positive, 10 negative themes); social support from family (42 studies [44 articles]: 30 positive [32 articles], 24 negative themes); social support from social network (36 studies [37 articles]: 22 positive [23 articles], 25 negative themes)

###### NIMHD framework: Interpersonal level – health care system domain

- Information and support from health care providers (44 studies [46 articles]: 36 positive [37 articles], 30 negative themes [31 articles])

###### NIMHD framework: Community level – physical/built environment domain

- Community resources and support: breastfeeding resources (29 studies [31 articles]: 16 positive [17 articles], 19 negative themes); community social support (25 studies [26 articles]: 19 positive [20 articles], 8 negative themes [9 articles])

###### NIMHD framework: Community level – sociocultural environment domain

- Cultural beliefs, practices, and norms (18 studies: 11 positive, 12 negative themes)

###### NIMHD framework: Community level – health care system domain

- Hospital practices (8 studies: 1 positive, 8 negative themes)
- Lack of support after discharge (4 studies: all negative themes)

###### NIMHD framework: Societal level – behavioral domain

- Maternity leave and breastfeeding laws (3 studies: 1 positive, 2 negative themes)

###### NIMHD framework: Societal level – sociocultural domain

- Breastfeeding in public (30 studies: 5 positive, 30 negative themes)
- Historical context (5 studies: 1 positive, 4 negative themes)

## Abstract

#### Background

Racial and ethnic disparities in human milk feeding practices are present in the United States.^a^,^b^,^c^ It is of interest to identify factors that may be associated with these disparities. To inform communication and program guidance on these topics, the Nutrition Evidence Systematic Review (NESR), housed in the Center for Nutrition Policy and Promotion (CNPP), Food and Nutrition Service (FNS), U.S. Department of Agriculture (USDA), conducted a rapid review project for the Office of Policy Support (OPS), FNS, USDA.

a Li R, Perrine CG, Anstey EH, Chen J, MacGowan CA, Elam-Evans LD. Breastfeeding trends by race/ethnicity among US children born from 2009 to 2015. JAMA Pediatr. 2019;173(12):e193319. doi:10.1001/jamapediatrics.2019.3319 31609438

b Chiang KV, Li R, Anstey EH, Perrine CG. Racial and ethnic disparities in breastfeeding initiation – United States, 2019. MMWR Morb Mortal Wkly Rep. 2021;70(21):769–774. doi:10.15585/mmwr.mm7021a1 34043611

c Jones KM, Power ML, Queenan JT, Schulkin J. Racial and ethnic disparities in breastfeeding. Breastfeed Med. 2015;10(4):186–196. doi:10.1089/bfm.2014.0152 25831234

One of the objectives of this project was to answer the following question: What factors are associated with racial and/or ethnic disparities in human milk feeding in the United States?

#### Methods

NESR analysts, in consultation with OPS, FNS, USDA, developed the rapid review protocols.

The types of data included were both quantitative and qualitative, the study participants were parent-infant dyads, the independent variable was race and/or ethnicity, and the outcomes were measures of human milk feeding initiation, human milk feeding duration, exclusive human milk feeding duration, meeting human milk feeding goals, and human milk feeding experiences (qualitative studies only). Further, to be included, studies must have examined one or more factors as mediators or moderators (quantitative data) or as variables or themes (qualitative data) in the association/relationship between race and/or ethnicity and the human milk feeding outcomes.

Additional inclusion criteria were that studies must: a) use a primary study design (i.e., reviews and meta-analyses were excluded), b) be published in English in peer-reviewed journals, c) be conducted in the United States, and d) enroll participants with a range of health statuses (i.e., studies which only included infants admitted to a neonatal intensive care unit were excluded).

The NESR librarian conducted a literature search in PubMed (MEDLINE), Web of Science, and CINAHL to identify articles published between January 2009 and June 2022. Based on the pre-determined inclusion and exclusion criteria, one NESR analyst screened all electronic results, while a second NESR analyst independently dual-screened 30 percent of the electronic results at the title and abstract level and verified inclusion or exclusion for all electronic results at the full-text level.

A NESR analyst extracted data from each included article, and a second analyst verified accuracy of key components of the extraction. For all articles examining quantitative data, one NESR analyst independently conducted a formal risk of bias assessment, by study design, for each included article, then a second NESR analyst reviewed the assessments for accuracy. The NESR analysts qualitatively synthesized the evidence, with attention given to the overarching themes or key concepts from the findings, similarities and differences between studies, and factors that may have affected the results. The evidence was organized based on the National Institute on Minority Health and Health Disparities (NIMHD) Research Framework.^d^ The NIMHD research framework combines two dimensions to categorize and assess health determinants: levels of influence (individual, interpersonal, community, societal) and domains of influence (biological, behavioral, physical/built environment, sociocultural environment, health care system). The NESR analysts assessed the evidence based on its risk of bias, consistency, directness, precision, and generalizability and then developed summary statements.

d Alvidrez J, Castille D, Laude-Sharp M, Rosario A, Tabor D. The National Institute on Minority Health and Health Disparities research framework. Am J Public Health. 2019;109:S16–S20. doi:10.2105/AJPH.2018.304883 30699025

#### Results

One hundred and forty-three articles (71 quantitative, 72 qualitative) met the inclusion criteria. For the quantitative studies, summary statements were developed by factor and by initiation and duration of human milk feeding within each factor. Summary statements were not drawn for qualitative studies due to the exploratory nature of these studies and the lack of statistical comparisons between racial and/or ethnic groups.

##### Quantitative studies

Among the 55 factors identified in the quantitative studies, there were 19 factors that had enough evidence to draw summary statements.

##### NIMHD framework: individual level – biological domain

###### Gestational age

- [underlined: Summary statement]: Evidence suggests that gestational age may not be associated with the relationship between race and ethnicity (Black, Hispanic, White) and human milk feeding initiation.
- [underlined: Summary of the evidence]: Five studies for human milk feeding initiation met the inclusion criteria. Both studies that examined mediation or moderation by interaction reported null findings, and there were mixed results for the two studies that stratified by race and ethnicity. There was no clear direction of results in the study that stratified by multiple factors.

###### Maternal BMI

- [underlined: Summary statement]: Evidence suggests that pre-pregnancy obesity, compared to a normal pre-pregnancy BMI, may be associated with lower human milk feeding initiation among White, but not Black, mothers. There is not enough consistent evidence to assess whether maternal BMI is associated with racial and ethnic disparities in human milk feeding duration.
- [underlined: Summary of the evidence]: Five studies for human milk feeding initiation and four studies for human milk feeding duration met the inclusion criteria. For initiation, although the two studies on moderation by interaction were mixed, most analyses that stratified by race and ethnicity suggest that pre-pregnancy BMI may moderate the relationship between race and ethnicity and human milk feeding initiation among White and Black mothers. For duration, studies varied in significance across analyses (mediation, moderation) and by the human milk feeding duration outcome.

###### Mode of delivery

- [underlined: Summary statement]: There is not enough consistent evidence among the small number of studies to determine whether mode of delivery is associated with racial and ethnic disparities in human milk feeding initiation.
- [underlined: Summary of the evidence]: Three studies (four articles) for human milk feeding initiation met the inclusion criteria. Study results were inconsistent, with both studies that examined interactions reporting non-significant interactions between delivery mode and race on initiation, and the two studies that stratified by race reporting inconsistent significant findings.

###### Postpartum depression

- [underlined: Summary statement]: Evidence suggests that postpartum depression may not be associated with the relationship between race and ethnicity in human milk feeding duration among Black, Hispanic, and White mothers.
- [underlined: Summary of the evidence]: Four studies for human milk feeding duration met the inclusion criteria. All three studies that examined mediation or moderation by interaction reported null findings and the one study that stratified by race and ethnicity found significant associations between postpartum depression and duration for both Black and White mothers.

##### NIMHD framework: individual level – behavioral domain

###### Smoking

- [underlined: Summary statement]: Evidence indicates that smoking is not associated with racial and ethnic disparities in human milk feeding initiation among Black, Hispanic, and White mothers. Evidence suggests that postpartum smoking may not be associated with racial and ethnic disparities in human milk feeding durations among Black, Hispanic, and White mothers.
- [underlined: Summary of the evidence]: Eight studies for human milk feeding initiation and four studies for human milk feeding duration met the inclusion criteria. For initiation, all six studies that examined moderation by interaction and that stratified the analysis by race and ethnicity found null results. For duration, three of four studies found null results and one study detected a significant interaction, which was supported by analyses stratified by race and ethnicity.

##### NIMHD framework: individual level – sociocultural environment domain

###### Income and income-related factors

- [underlined: Summary statement]: Evidence suggests that income and income-related factors may not be associated with the relationship between race and ethnicity and human milk feeding initiation among Black, Hispanic, and White mothers. There is not enough consistent evidence to determine whether associations between race and ethnicity and human milk feeding duration vary by income and income-related factors.
- [underlined: Summary of the evidence]: Seven studies for human milk feeding initiation and five studies for human milk feeding duration met the inclusion criteria. For initiation, the majority of studies that examined income and income-related factors were null. For duration, findings were inconsistent within each racial and ethnic comparison. Among the two studies on income, one study reported that income did not mediate the relationship between race and mean duration between Black and White mothers, while one study reported that income significantly mediated this relationship. The results for all other income-related factors were null.

###### Maternal age

- [underlined: Summary statement]: Evidence suggests that maternal age may not be associated with racial and ethnic disparities in human milk feeding initiation or duration.
- [underlined: Summary of the evidence]: Six studies for human milk feeding initiation and four studies for human milk feeding duration met the inclusion criteria. For initiation, all four studies on mediation or moderation by interaction found null results. Both studies that stratified by race and ethnicity reported significantly higher odds of initiation in older mothers compared to younger mothers among White but not Black mothers. For duration, three of four studies reported null findings.

###### Maternal education

- [underlined: Summary statement]: Evidence indicates that maternal education is not associated with racial and ethnic disparities in human milk feeding initiation among Black, Hispanic, and White mothers. Evidence suggests that lower levels of maternal education may be associated with shorter human milk feeding duration for Black mothers compared to White mothers.
- [underlined: Summary of the evidence]: Eleven studies for human milk feeding initiation and five studies for human milk feeding duration met the inclusion criteria. For initiation, the one study on mediation reported that maternal education significantly mediated differences in initiation between Black and White women, but not between Hispanic and Black or White mothers. All six studies that examined moderation by interaction and the majority of the studies that stratified by race and ethnicity suggested null moderation. For duration, all three studies on mediation reported that maternal education mediated the association between race and duration between Black and White women, with lower amounts of college education and shorter durations of human milk feeding among Black mothers. The one study that stratified by race and ethnicity reported null associations between maternal education and duration among Mexican and Black mothers.

###### Maternal nativity

- [underlined: Summary statement]: Evidence suggests that maternal nativity may be associated with the relationship between race and human milk feeding initiation among Black and White mothers, such that foreign-born Black mothers initiated human milk feeding at higher rates than US-born Black mothers, while associations were inconsistent for White mothers.
- [underlined: Summary of the evidence]: Six studies for human milk feeding initiation met the inclusion criteria. Both studies that tested interactions detected significant interactions between maternal nativity and race and ethnicity. Studies that examined analyses stratified by race and ethnicity reported greater initiation among foreign-born mothers compared to U.S.-born mothers, particularly for Black mothers, while findings were mixed for White mothers.

###### Parity

- [underlined: Summary statement]: Evidence suggests that parity may not be associated with racial and ethnic disparities in human milk feeding initiation and duration among Black, Hispanic, and White mothers.
- [underlined: Summary of the evidence]: Seven studies (eight articles) for human milk feeding initiation and four studies for human milk feeding duration met the inclusion criteria. For initiation, all four studies on mediation and moderation by interaction reported null results. For the two studies that stratified by race and ethnicity, there were no differences in the direction or significance of results across racial and ethnic groups. For duration, all studies found null results.

##### NIMHD framework: interpersonal level – biological domain

###### Birth weight

- [underlined: Summary statement]: There is not enough consistent evidence among the small number of studies to determine whether birth weight is associated with racial and ethnic disparities in human milk feeding duration.
- [underlined: Summary of the evidence]: Three studies for human milk feeding duration met the inclusion criteria. Results were mixed. Both studies on mediation reported that infant weight significantly mediated the association between race (Black versus White) and exclusive human milk feeding duration. For any human milk feeding duration, the studies that assessed mediation were mixed, with one study reporting that birth weight did not mediate the relationship between race and duration, and the other reporting that infant weight greater than or equal to 2500 grams mediated the relationship between race and any human milk feeding duration. The study that stratified by race and ethnicity reported that smaller proportions of Hispanic, White, and Black mothers breastfed for 6 months or longer if they had low birth weight compared to normal birth weight infants.

##### NIMHD framework: interpersonal level – behavioral domain

###### Employment

- [underlined: Summary statement]: Evidence suggests that employment or aspects of employment may not be associated with disparities in human milk feeding initiation between Black, Other, and White mothers. There is not enough consistent evidence among the heterogeneous variables related to employment to determine whether employment is associated with disparities in human milk feeding duration between Black and White mothers.
- [underlined: Summary of the evidence]: Three studies (four articles) for human milk feeding initiation and three studies (five articles) for human milk feeding duration met the inclusion criteria. For initiation, two of the three studies that examined mediation or moderation by interaction reported null results and the one study that stratified by race and ethnicity also reported null results. For duration, due to multiple analyses within studies, three of the five articles reported significant results, and four of the five reported null results.

##### NIMHD framework: interpersonal level – sociocultural environment domain

###### Marital status

- [underlined: Summary statement]: Evidence suggests that marital status may not be associated with racial and ethnic disparities in human milk feeding initiation. There is not enough consistent evidence among the small number of studies to determine whether marital status is associated with racial and ethnic disparities in human milk feeding duration.
- [underlined: Summary of the evidence]: Ten studies for human milk feeding initiation and three studies for human milk feeding duration met the inclusion criteria. For initiation, the one study on mediation had mixed findings, with marital status significantly mediating the relationship between race and initiation between Black and White mothers, but not for Hispanic versus White or Black mothers. Four of the five studies on moderation reported null interactions between Black, Hispanic, Other, and White mothers. The two studies that stratified by race and ethnicity were mixed, with one study reporting significantly higher odds of initiation with marriage among Black mothers while marital status was not retained in the model among White mothers, and the second study reporting significant associations in the same direction between marital status and initiation among all racial and ethnic groups examined. For duration, evidence was not consistent in significance.

###### Paternal race and ethnicity

- [underlined: Summary statement]: There is not enough consistent evidence among the small number of studies to determine whether paternal race and ethnicity is associated with racial and ethnic disparities in human milk feeding initiation.
- [underlined: Summary of the evidence]: Three studies for human milk feeding initiation met the inclusion criteria. All studies reported significant associations, and one study reported null associations due to multiple analyses. Among the significant findings, there are not enough studies for any particular comparison to evaluate trends consistently.

###### Social support

- [underlined: Summary statement]: There is not enough consistent evidence among the small number of studies to determine whether social support is associated with racial and ethnic disparities in human milk feeding duration.
- [underlined: Summary of the evidence]: Three studies for human milk feeding duration met the inclusion criteria. Three of the four analyses of social support variables were null, including breastfeeding discouragement, instrumental support, and emotional support. However, the type of social support (exclusive network or expansive network) was significant for Black mothers but not for White mothers.

##### NIMHD framework: community level – physical/built environment domain

###### Urbanicity

- [underlined: Summary statement]: There is not enough consistent evidence among the small number of studies to determine whether urbanicity is associated with racial and ethnic disparities in human milk feeding initiation.
- [underlined: Summary of the evidence]: Five studies for human milk feeding initiation met the inclusion criteria. All studies examined moderation and the results were mixed. For example, between Black and White mothers, three of four articles suggested that urbanicity did not moderate the relationship between race and initiation, while two studies suggested significant moderation of this relationship by urbanicity.

###### WIC participation

- [underlined: Summary statement]: Evidence suggests that prenatal or postpartum WIC participation may not be associated with the relationship between race and ethnicity and human milk feeding duration among Black, Hispanic, and White mothers. There is not enough consistent evidence to determine whether WIC participation is associated with racial and ethnic disparities in human milk feeding initiation.
- [underlined: Summary of the evidence]: Seven studies for human milk feeding initiation and six studies for human milk feeding duration met the inclusion criteria. For initiation, the one study on mediation reported that WIC participation did not mediate the relationship between race and ethnicity and initiation between Black, Hispanic, and White mothers. Among the moderation studies, findings for Black, White, and Other mothers were mixed, with two studies suggesting moderation and one study reporting no moderation. However, the directionality of results differed across the significant findings. Both studies on moderation reported higher initiation with WIC participation for Hispanic mothers compared to non-Hispanic mothers. For duration, one of the two studies on mediation reported null associations. Two of three studies on moderation by interaction, and the one study that stratified by race, also reported null results.

##### NIMHD framework: community level – health care system domain

###### Baby-friendly hospital practices

- [underlined: Summary statement]: Evidence suggests that baby-friendly hospital practices may not be associated with the relationship between race and ethnicity and human milk feeding initiation for Black, Hispanic, and White mothers. There is not enough consistent evidence among the small number of studies to determine whether baby-friendly hospital practices are associated with racial and ethnic disparities in human milk feeding duration.
- [underlined: Summary of the evidence]: Four studies for human milk feeding initiation and three studies for human milk feeding duration met the inclusion criteria. For initiation, the one study on mediation and the one study on moderation both reported null results, and three of the four studies that stratified by race and ethnicity also suggested that baby-friendly hospital practices did not moderate the relationship between race and ethnicity and initiation. For duration, all three studies reported both significant and null findings, with no clear pattern of results.

###### NICU admission

- [underlined: Summary statement]: There is not enough consistent evidence among the small number of studies to determine whether NICU admission is associated with racial and ethnic disparities in human milk feeding initiation.
- [underlined: Summary of the evidence]: Three studies for human milk feeding initiation met the inclusion criteria. The one study that tested an interaction did not detect significant moderation of the relationship between race and ethnicity and initiation. The remaining two studies, which stratified analyses by either race and ethnicity or NICU admission, suggested significant moderation, however the results were difficult to compare.

##### Qualitative studies

This portion of the rapid review includes 72 articles. Forty-five qualitative themes were identified and organized using the NIMHD research framework.

###### NIMHD framework: individual level – biological domain

- [underlined: Health issues] (10 studies: 2 positive, 9 negative themes): Positive breastfeeding themes related to infants experiencing digestion issue with formula. Negative breastfeeding themes related to mothers mentioning issues such as they were sick or were taking medication, or that their infant had health issues, such as staying in the NICU or potential allergy.
- [underlined: Physical breastfeeding problems] (39 studies: all negative): Commonly mentioned physical problems were insufficient milk supply, latching difficulties, and pain.

###### NIMHD framework: individual level – behavioral domain

- [underlined: Breastfeeding attitudes] (14 studies: 7 positive, 10 negative themes): This theme includes 14 studies, with 7 positive and 10 negative themes. Positive breastfeeding themes related to having positive attitudes towards breastfeeding, such as breastfeeding is natural or important. Negative breastfeeding themes related to feeling embarrassed, uncomfortable, and ambivalent about breastfeeding.
- [underlined: Breastfeeding being convenient or easy] (9 studies: 8 positive, 2 negative themes): Positive breastfeeding themes related to breastfeeding being convenient and easy, giving examples such as not having to prepare bottles and making night feedings easier. Negative breastfeeding themes related to misconception that breastfeeding was easy.
- [underlined: Breast milk is nutritionally unreliable or insufficient] (13 studies: all negative themes): Negative breastfeeding themes related to that breast milk was insufficient, inadequate, or did not provide enough nutrients for their baby, or believing that medications, negative emotions, or poor diet lead to a low quality breast milk.
- [underlined: Body image] (8 studies: all negative themes): Negative breastfeeding themes related to believing that breastfeeding affects their breast’s appearance, such as causing drooping, sagging, or changes in size.
- [underlined: Cost] (10 studies: 9 positive, 3 negative themes): Positive breastfeeding themes related to formula being expensive and that it was less expensive to breastfeed than to formula feed. Negative breastfeeding themes related to costs involved with breastfeeding.
- [underlined: Fear] (8 studies: all negative themes): Negative breastfeeding themes related to fear of pain with breastfeeding.
- [underlined: Health benefits] (42 studies [43 articles]: 42 positive, 1 negative themes): Positive breastfeeding themes related to health benefits of breastfeeding for the mother and infant and that breastfeeding is healthier. Negative breastfeeding theme related to concern that milk would be harmful, such as rotting the teeth of their infants.
- [underlined: Infant age] (2 studies: both negative themes): Negative themes related to mothers believing that the infant was old enough to stop breastfeeding or growing old.
- [underlined: Infant attachment] (7 studies: all negative themes): Negative breastfeeding themes related to concern that breastfeeding for too long of a duration would “spoil” the baby or lead to over-attachment.
- [underlined: Knowledge] (12 studies: 7 positive, 8 negative themes): Positive breastfeeding themes related to knowledge of how to latch, increase milk supply, and resolve breastfeeding issues, and knowledge of strategies to facilitate or make breastfeeding easier. Negative breastfeeding themes related to a lack of knowledge generally and on a variety of topics, such as breastfeeding dynamics (e.g., how to latch) and nipple sanitization, and acknowledged a lack of breastfeeding education.
- [underlined: Life demands and stress] (8 studies: all negative themes): Negative breastfeeding themes related to a variety of life demands and stresses such as stress due to mental health, home- and family-related stress and hardship, and poverty.
- [underlined: Lifestyle] (10 studies: 1 positive, 9 negative themes): Positive breastfeeding themes related to changing their own diet if their child had trouble breastfeeding. Negative breastfeeding themes related to lifestyle factors that they believed were incompatible with breastfeeding, including smoking, alcohol, diet, medications, and wanting freedom.
- [underlined: Not knowing if infant was adequately fed] (7 studies: all negative themes): Negative breastfeeding themes related to uncertainty about whether their infant was consuming enough breast milk or was adequately fed.
- [underlined: Time and responsibilities] (22 studies: 1 positive, 22 negative themes): Positive breastfeeding theme related to pumping was mentioned as a strategy to incorporate breastfeeding into a busy schedule. Negative breastfeeding themes related to breastfeeding being time consuming and that they did not have enough time to breastfeed due to busy schedules or other responsibilities such as other children and work.
- [underlined: Formula feeding attitudes] (4 studies: 3 positive, 3 negative themes): Positive breastfeeding themes related to negative attitudes or beliefs about formula. Negative breastfeeding themes related to formula being normal or familiar to them or that they did not have strong preferences for breastfeeding over formula feeding.
- [underlined: Convenience and ease of formula feeding] (13 studies: 1 positive, 12 negative themes): Positive breastfeeding themes related to formula not always being available. Negative breastfeeding themes related to formula being easier or more convenient than breastfeeding, particularly when returning to work.
- [underlined: Health benefits of formula feeding] (6 studies: all negative themes): Negative breastfeeding themes related to formula helping with infant growth, kept infants full, and helped infants sleep through the night.
- [underlined: Confidence] (15 studies: 10 positive, 10 negative themes): Positive breastfeeding themes related to breastfeeding self-efficacy, and that successful breastfeeding increased their self-confidence and sense of accomplishment. Negative breastfeeding themes related to low confidence or self-efficacy, including a lack of confidence or self-efficacy about dealing with breastfeeding discomfort and challenges.
- [underlined: Intention to breastfeed or formula feed] (6 studies: 6 positive, 2 negative themes): Positive breastfeeding themes related to intention or desire to breastfeed. Negative breastfeeding themes related to prenatal intention to formula feed or intending to breastfeed but encountering challenges.
- [underlined: Introduction to solid foods] (2 studies: both negative themes): Negative themes related to introducing solid foods as a sign of advanced development, to help the baby sleep, and making formula last longer.
- [underlined: Perseverance] (23 studies: 22 positive, 5 negative themes): Positive breastfeeding themes related to persistence and perseverance when encountering problems, such as overcoming pain and disregarding negative comments about breastfeeding from others. Negative breastfeeding themes related to giving up when encountering breastfeeding problems or challenges, not seeking support, and feeling overwhelmed when starting breastfeeding.
- [underlined: Previous BF experience] (10 studies: 10 positive, 1 negative themes): Positive breastfeeding themes related to positive impact of having successful previous breastfeeding experiences. Negative breastfeeding themes related to mothers having previous attempts at breastfeeding which were unsuccessful.

###### NIMHD framework: individual level – health care system domain

- [underlined: Cost of hospital lactation services] (1 study: 1 negative theme): Negative theme related to cost of a follow-up appointment for an in-patient lactation service, which deterred the mother from receiving assistance.

###### NIMHD framework: interpersonal level – behavioral domain

- [underlined: Infant preferences] (8 studies: 1 positive, 7 negative themes): Positive breastfeeding themes related to breastfeeding being preferred by and more satisfying for their infants compared to formula. Negative breastfeeding themes related to baby preferring bottles or formula to the breast or breastfeeding, and that their baby rejected the breast.
- [underlined: Sharing care of the infant] (12 studies: all negative themes): Negative breastfeeding themes related to being harder for other caregivers to feed the child, such as when returning to work, if breastfeeding instead of formula feeding.

###### NIMHD framework: interpersonal level – physical /built environment domain

- [underlined: Home environment] (3 studies: 1 positive, 3 negative themes): Positive breastfeeding themes related to having a private space at home. Negative breastfeeding themes related to a lack of privacy, lack of adequate housing, and desire to breastfeed in private (such as a in a bedroom).
- [underlined: Returning to work] (30 studies: 2 positive, 28 negative themes): Positive breastfeeding themes related to being able to pump at work and being a stay-at-home mother helped breastfeeding. Negative breastfeeding themes related to returning to work or school, with some studies reporting that formula feeding was easier for this transition and that returning to work led to insufficient milk supply.
- [underlined: Work environment] (23 studies: 10 positive, 19 negative themes): Positive breastfeeding themes related to environmental accommodations (e.g., lactation room, nursing station, fridge), time to pump, and supportive employers and coworkers. Negative breastfeeding themes related to facing challenges when at work, such as a lack of accommodations (e.g., suitable private locations, places to store milk) and time for pumping, fears about losing their job, and not having supportive employers and coworkers.

###### NIMHD framework: interpersonal level – sociocultural environment domain

- [underlined: Exposure to breastfeeding] (23 studies: 18 positive, 13 negative themes): Positive breastfeeding themes related to being exposed to breastfeeding through their family, and friends, including having a family history of breastfeeding, and that breastfeeding was normal in their social network. Negative breastfeeding themes related to a lack of exposure to breastfeeding from their friends and family, a lack of breastfeeding role models, and that breastfeeding was not a social norm.
- [underlined: Exposure to formula feeding] (6 studies: all negative themes): Negative themes related to formula being normal in their family and being exposed to formula feeding throughout life.
- [underlined: Sexualized view of breasts and breastfeeding] (7 studies: all negative themes): Negative breastfeeding themes related to believing that others (such as friends or their partner) had sexualized views of breasts or breastfeeding.
- [underlined: Social support from family] (42 studies from 44 articles: 30 positive from 32 articles, 24 negative themes): Positive breastfeeding themes related to receiving support from their mothers and other relatives through encouragement, advice and information, and having family role models. Negative breastfeeding themes related to a lack of support from family members, including negative comments, misinformation and worries from older generations, and a lack of hands-on or in-person support.
- [underlined: Social support from partner] (27 studies: 21 positive, 10 negative themes): Positive breastfeeding themes related to partner was supportive of breastfeeding and provided encouragement and social support. Negative breastfeeding themes related to a lack of support from their partner, including negative comments, social stigma, and opposition to breastfeeding.
- [underlined: Social support from social network] (36 studies [37 articles]: 22 positive [23 articles], 25 negative themes): Positive breastfeeding themes related to receiving social support from friends, social media, and other members of their community (e.g., church), such as through advice or information, stories, and encouragement. Negative breastfeeding themes related to feeling judgment about and opposition to breastfeeding from their social network, discouragement from friends, and a lack of discussion or encouragement from friends.

###### NIMHD framework: interpersonal level – health care system domain

- [underlined: Information and support from health care providers] (44 studies [46 articles]: 36 positive [37 articles], 30 negative themes [31 articles]): Positive breastfeeding themes related to receiving breastfeeding information, practical breastfeeding assistance, and breastfeeding encouragement or promotion from health care providers. Negative breastfeeding themes related to a lack of support from their health care provider, such as health care providers not encouraging breastfeeding, health care providers that are indifferent or discouraging, a lack of discussion about breastfeeding with health care providers, and stigma or discrimination by health care providers.

###### NIMHD framework: community level – physical/built environment domain

- [underlined: Breastfeeding resources] (29 studies [31 articles]: 16 positive [17 articles], 19 negative themes): Positive breastfeeding themes related to receiving breastfeeding information from the internet (including social media), magazines and books, and classes. Negative breastfeeding themes related to receiving free formula from WIC or the government.
- [underlined: Community social support] (25 studies [26 articles]: 19 positive [20 articles], 8 negative themes [9 articles]): Positive breastfeeding themes related to positive social support from social media, peer counselors, WIC representatives, and other breastfeeding mothers in their community, such as members of their church. Negative breastfeeding themes related to lack of social support from their community, including and social media.

###### NIMHD framework: community level – sociocultural environment domain

- [underlined: Cultural beliefs, practices, and norms] (18 studies: 11 positive, 12 negative themes): Positive breastfeeding themes related to breastfeeding being normal in their culture and that breastfeeding was intended by God. Negative breastfeeding themes related to sentiments such as that the breastfeeding culture in the United States is unsupportive, that their cultural practices related to breastfeeding were different than those of the United State more broadly, and that information and advice from their culture differed from that provided in the United States.

###### NIMHD framework: community level – health care system domain

- [underlined: Hospital practices] (8 studies: 1 positive, 8 negative themes): Positive breastfeeding theme related to rooming-in policies at hospitals. Negative breastfeeding themes related to formula given to them without consent or when the mother requested not to provide formula, or their infant despite mothers wanting to breastfeed.
- [underlined: Lack of support after discharge] (4 studies: all negative themes): Negative breastfeeding themes related to difficulty getting support or being reluctant to get support after being discharged from the hospital.

###### NIMHD framework: societal level – behavioral domain

- [underlined: Maternity leave and breastfeeding laws] (3 studies: 1 positive, 2 negative themes): Positive breastfeeding themes related to paid maternity leave and workplace protections for nursing mothers. Negative breastfeeding themes related to a lack of paid parental leave and a lack of maternity leave in the United States.

###### NIMHD framework: societal level – sociocultural domain

- [underlined: Breastfeeding in public] (30 studies: 5 positive, 30 negative themes): Positive breastfeeding themes related to feeling comfortable with breastfeeding in public, that having a cover increased comfort when breastfeeding in public, and that there were places that were supportive of breastfeeding in public. Negative breastfeeding themes related to breastfeeding in public was challenging due to stigma and feelings of embarrassment and discomfort, as well as a lack of convenient or supportive places to breastfeed in public.
- [underlined: Historical context] (5 studies: 1 positive, 4 negative themes): Positive breastfeeding themes related to pro-breastfeeding perspective to frame the historical context of breastfeeding. Negative breastfeeding themes related to Negative historical context of slavery and the exploitation of Black women as wet nurses.

## Results

The methods used to answer Key Question 2, What factors are associated with racial and/or ethnic disparities in human milk feeding in the United States?, are described in Chapter 1. Table 4 describes the analytic framework and Table 2 describes the inclusion and exclusion criteria for Key Question 2.

### Literature search and screening results

The literature search yielded 10,078 search results after the removal of duplicates (see Figure 7). Dual-screening resulted in the exclusion of 6,796 titles, 1,765 abstracts, and 1,283 full-texts articles. Reasons for full-text exclusion are in Appendix 5. The body of evidence included 234 articles across both Key Question 2 and Key Question 3 (see Chapter 4 for these results); Key Question 2 includes evidence from 143 articles (71 quantitative and 72 qualitative).

Figure 7 Literature search and screen flowchart

Literature search and screen flowchart The literature search in PubMed, CINAHL, and Web of Science retrieved 10,078 records after removing duplicates. 6,796 titles, 1,765 abstracts, and 1,283 full-texts were excluded. 234 articles were included in the systematic review: 143 for key question 2 (71 quantitative articles, 72 qualitative articles) and 91 for key question 3.

### Quantitative studies

Seventy-one articles met the inclusion criteria for Key Question 2 that examined quantitative data. The factors examined in these articles were organized using the NIMHD research framework (illustrated in Figure 8). Individual articles commonly addressed multiple factors.

Figure 8 Factors examined in quantitative articles included in Key Question 2 organized by the NIMHD research framework^*^ * Parentheses indicate the number of articles in which the themes were identified

This figure illustrates the factors examined in quantitative articles included key question 2 organized by the NIMHD research framework. Individual level - biological domain: diabetes/gestational diabetes (2 articles), gestational age (5 articles), gestational weight gain (1 article), hypertension (1 article), maternal BMI/pre-pregnancy obesity (8 articles), mode of delivery (5 articles) postpartum depression (5 articles). Individual level - behavioral domain: attitudes and beliefs (2 articles), early feeding practices (1 article), having a breastfeeding plan (1 article), information or knowledge of breastfeeding recommendation (2 articles), intention to breastfeed (2 articles), perceived control (1 article), smoking (10 articles), substance use during pregnancy (1 article), total stress factors (1 article). Individual level - sociocultural environment domain: income and income-related factors (8 articles), maternal age (8 articles), maternal education (13 articles), nativity and acculturation (7 articles), parity (9 articles). Individual level - health care system domain: contraception (1 article), insurance (4 articles). Interpersonal level - biological domain: birth weight (4 articles), child sex (1 article), infant health (1 article). Interpersonal level - behavioral domain: employment (7 articles), violence exposure (2 articles). Interpersonal level - physical/built environment domain: household environment (2 articles). Interpersonal level - sociocultural environment: coresident father (2 articles), coresident grandparent (1 article), paternal education (1 article), paternity acknowledgement (1 article), paternal race/ethnicity (3 articles), paternal nativity (1 article), marital status (11 articles), maternal or paternal grandmother breastfed their own child (1 article), mother/partner as primary caretaker (1 article), social support (3 articles), subjective norms (1 article). Community level - biological domain: coronavirus pandemic (1 article). Community level - physical/built environment domain: geographic location (1 article), military affiliation (1 article), neighborhood characteristics (2 articles), urbanicity (5 articles), WIC participation (11 articles). Community level - health care system domain: baby-friendly hospital practices (5 articles), breastfeeding information from hospital staff (2 articles), hospital level of perinatal care (1 article), labor anesthesia (1 article), medical conditions or labor/delivery complications (1 article), NICU (3 articles), prenatal care (2 articles), type of birth attendant (1 article). Societal level - behavioral domain: maternity leave length (2 articles).

| NIMHD Level
NIMHD Domain | Individual | Interpersonal | Community | Societal
Biological | Diabetes/gestational diabetes (2); Gestational age (5); Gestational weight gain (1); Hypertension (1); Maternal BMl/pre-pregnancy obesity (8); Mode of delivery (5); Postpartum depression (5) | Birth weight (4); Child sex (1); Infant health (1) | Coronavirus pandemic (1)
Behavioral | Attitudes and beliefs (2); Early feeding practices (1); Having a breastfeeding plan (1); Information or knowledge of breastfeeding recommendation (2); Intention to breastfeed (2); Perceived control (1); Smoking (10); Substance use during pregnancy (1); Total stress factors (1) | Employment (7); Violence exposure (2) | | Maternity leave length (2)
Physical/Built environment | | Household environment (2) | Geographic location (1); Military affiliation (1); Neighborhood characteristics (2); Urbanicity (5); W1C participation (11)
Sociocultural environment | Income and income-related factors (8); Maternal age (8); Maternal education (13); Nativity and acculturation (7} Parity (9) | Coresident father (2); Coresident grandparent (1); Paternal education (1); Paternity acknowledgement (1); Paternal race/ethnicity (3); Paternal nativity (1); Marital status (11); Maternal or paternal grandmother breastfed their own child (1); Mother/partner as primary caretaker (1); Social support (3); Subjective norms (1)
Health care system | Contraception (1); Insurance (4) | | Baby-friendly hospital practices (5); Breastfeeding information from hospital staff (2); Hospital level of perinatal care (1); Labor anesthesia (1); Medical conditions or labor/delivery complications (1); NICU (3); Prenatal care (2); Type of birth attendant (1)

#### Description of the evidence

This rapid review includes 71 articles^1–71^ that examined whether certain factors mediated or moderated the relationship between race and/or ethnicity and human milk feeding outcomes using quantitative data (study characteristics presented in Table 13). Among the 71 quantitative articles, 26 articles (37 percent) were prospective cohort studies (PCS),^3–5,7,15,18–20,27,32–34,36,39,42–45,49,50,52–54,62,65,66^ 5 articles (7 percent) were retrospective cohort studies (RCS),^10,12,14,38,55^ and 40 articles (56 percent) were cross-sectional studies.^1,2,6,8,9,11,13,16,17,21–26,28–31,35,37,40,41,46–48,51,56–61,63,64,67–71^ Analytic sample sizes in these studies ranged from 205 to 1,317,535. Fifteen articles (21 percent) had sample sizes less than 1,000^6–8,12,15,23,25,34,44,45,49,52,64–66^; 21 articles (28 percent) had sample sizes from 1,000 up to 10,000^11,13,14,18,19,22,24,30,31,36,37,40,41,43,47,48,50,54,62,63,67^; 20 articles (28 percent) had sample sizes from 10,000 up to 100,000^2–5,10,17,20,26,27,33,35,42,51,53,56,61,68–71^; and 14 articles (20 percent) had sample sizes greater than 100,000,^1,9,16,21,28,29,38,39,46,55,57–60^ including 5 articles that had sample sizes greater than 1,000,000.^9,16,21,57,59^ One study did not report sample sizes.^32^ The most common cohorts were the Pregnancy Risk Assessment Monitoring System (PRAMS) in 15 articles,^4,14,20,22,33,37,38,40–42,51,56,61,63,68^ followed by the Early Childhood Longitudinal Study – Birth Cohort (ECLS-B) in 6 articles.^5,31,32,47,53,54^ Three articles examined each of the following cohorts: Infant Feeding Practices Study II (IFPS II),^15,19,62^ National Survey of Children’s Health (NSCH),^2,35,70^ National Survey of Family Growth (NSFG),^11,30,67^ and Ohio Vital Statistics.^16,28,29^ Two articles examined each of the following cohorts: National Health and Nutrition Examination Survey (NHANES),^24,48^ Panel Study of Income Dynamics (PSID),^65,66^ Pregnancy Nutritional Surveillance System (PNSS),^26,39^ and Vital Statistics Natality Birth database.^59,60^

##### Population

The most common racial and ethnic comparisons were between Black or African American, Hispanic, and/or White mothers. Participants in 20 articles were from national samples.^2,5,24,30–32,35,38,47,48,50,51,53,56,59,62,65–67,70^ Other studies were conducted within individual states. The most commonly examined states were Ohio,^8,14,16,28,29,45^, North Carolina,^4,33,34,39,64^ Massachusetts,^1,4,9,21,33^ New York,^17,23,33,46,64^ and Pennsylvania.^4,13,36,44^ Fifteen articles exclusively included or included a majority of participants with low income^7,12,15,23,25,31,43,64^ or who were WIC-eligible or WIC-participating.^12,18,26,39,40,48,54,71^ Three articles included only first-time mothers^40,59,60^ and two articles included only adolescent mothers.^11,52^

##### Exposures

The factors examined by the studies were organized by the NIMHD framework.

Within the individual level and biological domain, the following factors were identified: maternal body mass index (BMI),^22,28,31,34,37,42,45,57^ gestational age,^28,34,40,43,67^ postpartum depression,^22,34,36,43,68^ mode of delivery,^22,28,34,40,61^ diabetes,^29,55^ hypertension,^45^ and gestational weight gain.^34^

Within the individual level and behavioral domain, the following factors were identified: smoking,^7,10,13,25,34,36,40,43,56,63^ attitudes and beliefs,^43,50^ intention to breastfeed,^36,45^ having a breastfeeding plan,^23^ perceived control,^50^ information^50^ or knowledge of breastfeeding recommendation,^62^ early feeding practices,^24^ total stress factors,^40^ and substance use (not smoking) during pregnancy.^10^

Within the individual level and sociocultural environment domain, the following factors were identified: acculturation and nativity,^1,12,18,21,25,36,70^ maternal age,^13,28,34,36,40,43,50,52^ maternal education,^7,13,18,25,28,30,31,34,36,40,43,45,50^ income and income-related factors,^30,31,36,40,43,45,48,67^ and parity.^4,13,27,28,34,36,40,43,50^

Within the individual level and health care system domain, the following factors were identified: insurance^28,40,44,45^ and contraception.^8^

Within the interpersonal level and biological domain, the following factors were identified: birth weight,^5,40,45,50^ child sex,^51^ and infant health.^36^

Within the interpersonal level and behavioral domain, the following factors were identified: employment,^22,34,40,43,50,65,66^ and violence exposure.^23,40^

Within the interpersonal level and physical/built environment domain, the following factors were identified: household environment-related variables,^36,40^ including insufficient privacy/space in home,^36^ unstable housing before birth,^36^ number of people living with mother,^40^ recent move prior to pregnancy,^40^ and rooms in the residence.^40^

Within the interpersonal level and sociocultural environment domain, the following factors were identified: coresident father,^11,43^ coresident grandparent,^43^ paternal education,^36^ paternity acknowledgement,^59^ paternal race and ethnicity,^9,49,60^ paternal nativity,^9^ marital status,^13,28,30,34,36,40,43,45,60,61,67^ maternal or paternal grandmother breastfed their own child,^43^ social support,^6,14,64^ mother/partner as primary caretakers,^50^ and subjective norms.^50^

Within the community level and biological domain, the following factor was identified: coronavirus pandemic.^17^

Within the community level and physical/built environment domain, the following factors were identified: geographic location (mothers dwelling in the United States-Mexico border versus mothers who are not dwelling in the United States-Mexico Border),^58^ military affiliation,^38^ neighborhood characteristics,^35,69^ urbanicity,^20,26,39,40,53^ and WIC participation.^13,15,18,28,36,41,43,50,53,54,71^

Within the community level and health care system domain, the following factors were identified: baby-friendly hospital practices,^2,3,40,43,45^ neonatal intensive care unit (NICU),^13,16,28^ breastfeeding information from hospital staff,^36,40^ type of birth attendant,^19^ prenatal care,^28,40^ hospital level of perinatal care,^46^ labor anesthesia,^13^ and medical conditions or labor/delivery complications.^32^

Within the societal level and behavioral domain, the following factor was identified: maternity leave length.^33,47^

##### Outcomes

The outcomes examined in the studies were: human milk feeding initiation (58 articles),^1–5,7–11,13,14,16–21,23,25–31,33–43,46–49,51–53,55,57–63,65–67,69–71^ which included breastfeeding at hospital discharge and breastfeeding for at least 1 week; any (33 articles)^2,4–7,11,12,14,20,23–25,31–33,36–38,41,43–45,48,50–52,54,62,64–66,68,71^ and exclusive (15 articles)^6,12,15,19,22,23,35,44,45,49,50,52,56,64,68^ human milk feeding duration (36 articles total),^2,4–6,11,12,14,15,19,20,22–25,31–33,35–38,41,43–45,48–52,54,56,64–66,68^ assessed continuously and categorically between 2 weeks to 12 months; and meeting human milk feeding goals (1 article).^45^

Table 13 Description of studies that examined whether certain factors mediated or moderated the relationship between race and/or ethnicity and human milk feeding outcomes (Key Question 2)^*^

Study | Cohort name | Study design | Analytic sample size | Location | Population | Race and/or ethnicity | Outcomes examined
Abuelezam, 2020^1^ | MA Standard Certificate of Live Birth 2012-2016 | CS | 207,458 | MA | Live births in MA 2012-2016 | Arab-American: 4%; Non-Hispanic White: 96% | BF Initiation
Belanoff, 2012^2^ | NSCH 2007 | CS | 25,036 | United States | National sample | Hispanic: 10%; Missing: 2%; Non-Hispanic Black: 12%; Non-Hispanic Other: 22%; Non-Hispanic White: 54% | BF Initiation; BF Duration to at Least; 6 mo
Bramson, 2010^3^ | - | PCS | 21,842 | San Bernardino and Riverside Counties, CA | 95% of births at participating hospitals | African American: 6%; Caucasian: 32%; Hispanic: 57%; Other: 6% | EBF During Maternity Hospitalization
Buckman, 2020^4^ | PRAMS 2016-2017 | PCS | 20,694 | 14 States (CT, DE, GA, MA, MD, MO, MT, NC, NE, NJ, PA, SD, UT, and WI) | Random sample | Hispanic: ~14%; Non-Hispanic Black: ~14%; Non-Hispanic White: ~63%; Other: ~9% | BF Initiation; BF Discontinuation in wk
Campbell, 2018^5^ | ECLS-B & NSCH | PCS | 44,155 | United States | National representative sample | Black: 14%; Hispanic: 27%; White: 58% | BF Initiation; BF ≥6 mo
Carlin, 2021^6^ | - | CS | 402 | Washington D.C. | Black or White mothers | Black: 67%; White: 33% | BF at 2 wk; EBF at 2 wk
Carswell, 2018^7^ | - | PCS | 247 | Memphis, TN | Population with low income who reported smoking month prior to pregnancy | African American: 40%; Asian: <1%; Biracial/Multiracial: 2%; Caucasian: 57%; Hispanic: <1%; Other (NR): <1% | Ever BF
Chen, 2016^8^ | - | CS | 919 | Cleveland, OH | Urban hospital patients | African American: 77%; Non-African American: 23% | BF Initiation
Cheng, 2018^9^ | MA Standard Certificate of Live Births 1996-2010 | CS | 1,053,096 | MA | Live births in MA 2012-2016 | African: 1%; African American: 3%; American Indian:; Asian Indian: 2%; Brazilian: 2%; Cambodian: <1%; Cape Verdean: <1%; Chinese: 2%; Columbian: <1%; Dominican: 2%; European: 20%; Filipino: <1%; Haitian: 1%; Jamaican: <1%; Japanese: <1%; Korean: <1%; Lebanese: <1%; Mexican: <1%; Native American: <1%; Other: 3%; Other Asian/Pacific Islander: <1%; Other Central American: 1%; Other Hispanic/Latina: <1%; Other Middle Eastern: <1%; Other Portuguese: 2%; Other South American: <1%; Other West Indian/Caribbean: <1%; Puerto Rican: 5%; Salvadoran: 1%; Vietnamese: <1%; White: 47% | BF Initiation
Chung, 2021^10^ | OB COAP | RCS | 84,742 | MT, WA | Random sample | American Indian/Alaska Native: 1%; Asian/Native Hawaiian or Pacific Islander: 19%; Black or African American, non-Hispanic: 6%; Hispanic: 17%; Missing: 2%; Multi-race/Other: 4%; White, Non-Hispanic: 53% | EBF at Discharge
Corsack, 2022^11^ | NSFG 2011-2017 | CS | 1,867 | United States | Individuals who gave birth during adolescence (15-19 y) | Hispanic: 31%; Non-Hispanic Black: 21%; Non-Hispanic Other: 6%; Non-Hispanic; White: 42% | BF Initiation; BF Duration
Dabritz, 2009^12^ | - | RCS | 379 | Yolo County, CA | High proportion of low-income individuals (68% received WIC) | Hispanic: 54%; Other ethnicity: 10%; White: 35% | Partial BF at 6 mo; Almost EBF at 6 mo
Demirci, 2013^13^ | PA Birth Certificates (PA Department of Health) 2009 | CS | 7,012 | PA | Late-preterm infants | Black: 18%; Hispanic: 9%; Not Hispanic: 91%; Other: 10%; White: 71% | BF Non-initiation
Fabiyi, 2021^14^ | PRAMS 2004, 2005, 2009, 2010 | RCS | 5,378 | FL, LA, OH | Random sample | Hispanic: 20%; Non-Hispanic Black: 18%; Non-Hispanic White: 62% | BF Initiation; BF Duration at 4 wk; BF Duration at 10 wk
Francescon, 2016^15^ | IFPS II 2005 to 2007 | PCS | 784 | United States | Individuals with low income | Hispanic: 6%; Non-Hispanic Black: 6%; Non-Hispanic White: 85%; Other: 3% | EBF at 3 mo
Gertz, 2019^16^ | Ohio Vital Statistics 2006-2015 | CS | 1,317,535 | OH | Live births in OH 2006-2015 | Hispanic: 5%; Non-Hispanic Black: 16%; Non-Hispanic White: 76%; Other: 3% | BF Non-Initiation
Glazer, 2022^17^ | - | CS | 13,571 | New York, NY | Singleton, term births not admitted to the NICU | Latina: 17%; Non-Latina Asian: 11%; Non-Latina Black: 12%; Non-Latina White: 53%; Other/Unknown: 8% | EBF in Hospital
Gyllstrom, 2021^18^ | - | PCS | 4,906 | MN | WIC participants | Black: 20%; Hispanic: 16%; White: 61%; Other: 3% | BF Initiation
Haile, 2017^19^ | IFPS II 2005-2007 | PCS | 2,026 | United States | National sample | Hispanic: 7%; Non-Hispanic Black: 4%; Non-Hispanic White: 85%; Other: 5% | EBF at Discharge; EBF at 3 mo
Hamilton, 2020^20^ | PRAMS 2004-2013 | PCS | 11,851 | GA | Random sample | Hispanic: 11%; Non-Hispanic Black: 44%; Non-Hispanic White: 40%; Other: 5% | BF Initiation; BF Duration ≥ 8 wk
Hawkins, 2014^21^ | Registry of Vital Records and Statistics (MA) 1996-2009 | CS | 1,067,375 | MA | Live births in MA | NR; 31 ethnic groups examined | BF Initiation
Hayes, 2014^22^ | PRAMS, 2004-2008 | CS | 8,508 | HI | Random sample based on HI birth certificates | Black: 2%; Chinese: 4%; Filipino: 18%; Japanese: 12%; Korean: 2%; Native Hawaiian: 28%; Other/unknown: 10%; Samoan: 3%; White: 21% | Exclusive BF for 8 wk
Holland, 2018^23^ | - | CS | 450 | Upstate NY | Individuals receiving care at low-income serving pediatric or family medicine practices | Black: 44%; Hispanic: 27%; White: 29% | BF Initiation; BF Duration at 4 wk; BF Duration at 13 wk; EBF Duration at 4 wk; EBF Duration at 13 wk
Holmes, 2011^24^ | NHANES 1999-2006 | CS | 4,480 | United States | National Sample | Black: NR; Hispanic: NR; Other: NR; White: NR | BF Duration
Hughes, 2019^25^ | Sinai Community Health Survey 2.0 | CS | 551 | Chicago, IL | Individuals living in predominantly low-income neighborhoods | Mexican: 40%; Non-Hispanic Black: 47%; Non-Hispanic White: NR; Puerto Rican: 13% | BF Initiation; BF Duration ≥ 6 mo
Jacobson, 2015^26^ | PNSS | CS | 17,067 | KS | WIC participants | American Indian: 1%; Asian or Hawaiian/Pacific Islander: 3%; Hispanic: 28%; Multi-racial: 2%; Non-Hispanic Black: 11%; Non-Hispanic White: 56% | BF Initiation
Jolles, 2022^27^ | AABC Perinatal Data Registry 2007-2020 | PCS | 70,927 | NR | National sample | American Indian: <1%; Asian: 2%; Black: 8%; Hawaiian/Pacific Islander: <1%; Hispanic: 12%; Mixed race: 1%; Undisclosed: 4%; White: 72% | EBF at Discharge
Kachoria, 2014a^29^ | Ohio Vital Statistics 2006-2011 | CS | 744,899 | OH | Live births in OH | Hispanic: 4%; Non-Hispanic Black: 16%; Non-Hispanic Other: 2%; Non-Hispanic; White: 78% | BF at Discharge
Kachoria, 2014b^28^ | Ohio Vital Statistics 2006-2011 | CS | 501,967 | OH | Live births in OH | Hispanic: 4%; Missing: 2%; Non-Hispanic Black: 16%; Non-Hispanic Other: 2%; Non-Hispanic White: 77% | BF Initiation
Kirksey, 2021^30^ | NSFG, 1973, 1982, 1995, 2006, 2015 | CS | 6,859 | United States | National sample | Black: ~32%; Hispanic: ~15%; Other: ~6%; White: ~61% | BF Initiation
Kitsantas, 2010^32^ | ECLS-B | PCS | NR | United States | National sample | Black: 15%; Hispanic: 21%; Other: 4%; White: 60% | BF Duration
Kitsantas, 2011^31^ | ECLS-B | CS | unweighted: 8,550; weighted: 5,000 | United States | National sample, low and middle income | Non-Hispanic Black: NR; Hispanic: NR; Non-Hispanic White: NR | BF Initiation; BF Duration ≥ 2 mo; BF Duration ≥ 4 mo
Kortsmit, 2021^33^ | PRAMS 2016-2018 | PCS | 12,301 | MA, MD, MN, MO, NC, NH, NY (including NYC), VT, WI | Random sample | Hispanic: 10%; Non-Hispanic Black: 18%; Non-Hispanic Other: 13%; Non-Hispanic White: 59% | BF Initiation; Any BF at 1, 2, 3 mo
Krause, 2011^34^ | Active Mothers Postpartum | PCS | 450 | Durham, NC | Postpartum women with overweight or obesity | Black: 45%; White/other: 55% | BF Initiation
Kummer, 2020^35^ | NSCH 2011-2012 | CS | 29,829 | United States | National random sample | Black, Non-Hispanic: 9%; Hispanic: 16%; Other/Multiracial, Non-Hispanic: 13%; White, Non-Hispanic: 62% | BF Initiation; EBF for 6 mo
Lee, 2009^36^ | Philadelphia Department of Public Health District Health Centers | PCS | 1,140 | Philadelphia, PA | None | Foreign-born Black 8%; Non-Hispanic native-born Black 64%; Non-Hispanic White 10%; Other Hispanic 9%; Puerto Rican 9% | BF for at Least 1 wk; BF Duration up to 8 mo
Liu, 2010^37^ | SC PRAMS 2000-2005 | CS | 6,357 | SC | None | Black: 45%; White: 55% | BF Initiation; BF Discontinued; Within 6 mo
Lundquist, 2015^38^ | PRAMS 1995-2005 | RCS | 313,439 | United States | National sample | Asian-Civilian: 3%; Asian-Military: 6%; Black-Civilian: 17%; Black-Military: 18%; Latina-Civilian: 14%; Latina-Military: 8%; Other-Civilian: 1%; Other-Military: 2%; White-Civilian: 64%; White-Military: 65% | BF Initiation (>1 wk); BF Duration at 16 wk
Lynch, 2012^39^ | PNSS | PCS | 240,054 | NC | WIC mothers | Hispanic: 22%; Non-Hispanic Black: 35%; Non-Hispanic White: 43% | BF Initiation
Ma, 2012^40^ | LA PRAMS 2000-2004 | CS | 2,036 | LA | WIC enrolled first-time mothers | Black: 53%; White: 47% | BF Initiation
Marshall, 2013^41^ | PRAMS 2004-2008 | CS | 3,221 | MS | Stratified sample | Black: 53%; Non-Hispanic: 97%; White: 47% | BF Initiation; BF Duration at 10 wk
Masho, 2015^42^ | PRAMS 2009-2011 | PCS | 95,141 | United States | Random sample | Hispanic: 18%; Non-Hispanic, Black: 13%; Non-Hispanic other: 8%; Non-Hispanic White: 61% | BF Initiation
McKinney, 2016^43^ | CCHN study | PCS | 1,636 | Baltimore, MD; Washington DC; Lake County, IL | Low SES | Black: 56%; Hispanic-English-speaking: 9%; Hispanic-Spanish-speaking: 16%; White: 19% | BF Initiation; BF Duration at 6 mo
Mercier, 2018^44^ | - | PCS | 405 | Philadelphia, PA | Mothers with any insurance | African American: 51%; Asian: 10.4%; Hispanic: 10.4%; White: 28.2% | Any BF at 6-8 wk; EBF at 6-8 wk
Morrow, 2021 | PREVAIL cohort | PCS | 205 | Cincinnati, OH | Generally healthy mother-child pairs | Black: 45%; White: 55% | EBF at 6 wk; BF at 6 mo; Meeting Intention to BF for 6 mo
Nguyen, 2017^46^ | NY Statewide Perinatal Data System (2014 birth certificates) | CS | 154,583 | NY | Infants who breastfed | African American, non-Hispanic: 14%; Any race, Hispanic: 25%; Asian American, non-Hispanic: 11%; Other race, non-Hispanic: 2%; White, non-Hispanic: 49% | EBF at hospital
Ogbuanu, 2011^47^ | ECLS-B | CS | 6,150 | United States | Nationally representative sample who worked 12 mo before delivery | Black, Non-Hispanic: 14%; Hispanic: 19%; Other, Non-Hispanic: 6%; White, Non-Hispanic: 61% | BF Initiation
Orozco, 2020^48^ | NHANES 2009-2014 | CS | 2,069 | United States | National sample (87% WIC participants) | Hispanic: 38%; Non-Hispanic Black: 20%; Non-Hispanic White: 31%; Other: 11% | BF Initiation; BF Duration (mean)
Pithia, 2021^49^ | - | PCS | 499 | Los Angeles, CA | Infants admitted to newborn nursery with risk factors for severe hyperbilirubinemia | African American: 5%; American Indian/Alaska; Native: <1%; Asian: 16%; More than one Race: 1%; Native Hawaiian/Pacific Islander: <1%; Other: <1%; White: 76%; Non-Hispanic Ethnicity: 71% | EBF at Discharge; EBF at 30 d
Safon, 2021^50^ | SAFE 2011-2014 | PCS | 2,050 | United States | National sample | Foreign-born Black: 7%; U.S.-born Black: 33%; U.S.-born White: 60% | Any BF at 2-6 mo; Exclusive BF at 2-6 mo
Shafer, 2017^51^ | PRAMS 2009-2010 | CS | 66,107 | United States | National random sample | Alaskan Native: <1%; American Indian: 2%; Black: 16%; Chinese: 1%; Filipino: 1%; Hawaiian: 1%; Hispanic: 14%; Japanese: <1%; Mixed race: 3%; Non-Hispanic other non-white: <1%; Other Asian: 4%; White: 54% | BF Initiation; BF Duration
Sipsma, 2013^52^ | - | PCS | 225 | CT | Adolescents (14-21 y) | Hispanic: 42%; Non-Hispanic Black: 40%; Non-Hispanic White/Other: 18% | BF Initiation; BF Duration; EBF Duration
Sparks, 2010^53^ | ECLS-B | PCS | 10,550 | United States | National Sample | Asians: 4%; Foreign born Mexican-origin Hispanic: 10%; Native Americans: <1%; Non-Hispanic Black: 15%; Non-Hispanic White: 60%; Other Hispanics: 7%; U.S. born Mexican-origin Hispanic: 5% | BF Initiation
Sparks, 2011^54^ | ECLS-B | PCS | 3,550 | United States | WIC-eligible | Asians: 11%; Foreign born Mexican-origin Hispanic: 14%; Native Americans: 7%; Non-Hispanic Black: 18%; Non-Hispanic White: 37%; Other Hispanics: 7%; U.S. born Mexican-origin Hispanic: 6% | BF Duration at 1-12 mo
Stevens, 2019^55^ | - | RCS | 517,800 | SC | State sample | Hispanic: 10%; Non-Hispanic Black: 33%; Non-Hispanic White: 57% | BF Initiation
Tanda, 2018^56^ | PRAMS 2009-2011 | CS | 72,861 | United States | National sample | Hispanic: 18%; Non-Hispanic Black: 14%; Non-Hispanic White: 61%; Others: 8% | EBF ≥12 wk
Thompson, 2013^57^ | FL birth certificates 2004-2009 | CS | 1,161,949 | FL | Live births in FL 2004-2009 | Black: 18%; Hispanic: 32%; Other: 4%; White: 46% | BF Initiation
Walker, 2014^58^ | TX birth certificates 2009 (TX Department of State Health Services) | CS | 250,857 | TX | Live births in TX 2009 | Hispanic: 58%; Non-Hispanic White: 42% | BF Initiation
Wallenborn, 2017a^61^ | PRAMS 2004-2011 | CS | 34,854 | United States | Prior cesarean-section | Black, Non-Hispanic: 15%; Hispanic: 19%; Other, Non-Hispanic: 7%; White, Non-Hispanic: 60% | BF Non-Initiation
Wallenborn, 2017b^62^ | IFPS II 2005-2007 | PCS | 2,935 | United States | National Sample | Non-Hispanic Black: 5%; Hispanic: 6%; Other: 5%; Non-Hispanic White: 85% | Any BF; EBF at Hospital Discharge
Wallenborn, 2018^59^ | Vital Statistics Natality Birth database 2014 | CS | 1,127,861 | United States | National sample of women’s first birth | Hispanic: 17%; Non-Hispanic Black: 14%; Non-Hispanic Multiracial: 2%; Non-Hispanic Other: 6%; Non-Hispanic White: 60% | BF Non-initiation
Wallenborn, 2019^60^ | Vital Statistics Natality Birth database 2014 | CS | 840,887 | United States | First-time mothers | NR | BF Initiation
Weiser, 2009^63^ | MO PRAMS 2005 | CS | 1,789 | MO | Stratified, random sample | Black: 9%; White, other: 91% | BF Initiation
White, 2022^64^ | Greenlight Study | CS | 826 | Miami, FL; Nashville, TN; New York, NY; Chapel Hill, NC | Predominantly low-income | Hispanic: 50%; Non-Hispanic Black: 27%; Non-Hispanic Other (American Indian/Alaskan Native): <1%; Non-Hispanic Other (Asian): 2%; Non-Hispanic Other (Other) 2%; Non-Hispanic White: 18% | Any BF at 2 mo; EBF at 2 mo
Whitley, 2021^66^ | PSID 2007-2015 | PCS | 970 | United States | Nationally representative sample | Black: 14%; Other Races: 17%; White: 69% | BF Initiation; BF Duration
Whitley, 2022^65^ | PSID 2007-2015 | PCS | 631 | United States | National sample | Black: 35%; Other: 12%; White: 53% | BF Initiation; BF Duration at 6 mo
Wiener, 2016^67^ | NSFG 2011-2013 | CS | 5,397 | United States | National sample | Hispanic: 32%; Non-Hispanic Black: 24%; Non-Hispanic White: 43% | BF for at Least 1 wk
Wouk, 2017^68^ | PRAMS 2010-2011 | CS | 44,294 | United States | Random sample | Asian: ~7%; Black: ~16%; Hispanic: ~15%; Missing: ~5%; Other: ~8%; White: ~50% | EBF at 3 mo
Yourkavitch, 2018^69^ | NJ birth certificates 2006 | CS | 77,502 | NJ | Live birth in NJ 2006 | Asian/Pacific Islander: 11%; Black: 12%; Hispanic: 28%; White: 48% | Any BF at Hospital Discharge; EBF at Hospital Discharge
Yu, 2013^70^ | NSCH 2007 | CS | 91,532 | United States | National sample | Hispanic: 17%; Multirace: 4%; Non-Hispanic Black: 15%; Non-Hispanic White: 59%; Other: 5% | BF Initiation
Zhang, 2021^71^ | NIS-Child 2006-2016 | CS | 92,335 | United States | WIC-eligible sample | Hispanic: 37%; Non-Hispanic Black: 17%; Non-Hispanic White: 36%; Other: 10% | BF Initiation

* Abbreviations: %, percent; &, and; AABC, American Association of Birth Centers; BF, breastfeeding or breastfed; CCHN, Community and Child Health Network; CS, cross-sectional; d, day; EBF, exclusive breastfeeding or exclusively breastfed; ECLS-B, Early Childhood Longitudinal Study, Birth Cohort; IFPS II, Infant Feeding Practices Study II; mo, month; NHANES, National Health and Nutrition Examination Survey; NICU, Neonatal Intensive Care Unit; NIS-Child, National Immunization Survey – Child; NR, not reported; NSCH, National Survey of Children’s Health; NSFG, National Survey of Family Growth; OB COAP, Obstetrical Care Outcomes Assessment Program; PCS, Prospective cohort study PNSS, Pregnancy Nutritional Surveillance System; PRAMS, Pregnancy Risk Assessment Monitoring System; PREVAIL, Pediatric Respiratory and Enteric Virus Acquisition and Immunogenesis Longitudinal; PSID, Panel Study of Income Dynamics; RCS, Retrospective cohort study; SAFE, Study of Attitudes and Factors Effecting Infant Care Practices; SES, socioeconomic status; WIC, Special Supplemental Nutrition Program for Women, Infants, and Children; wk, week; y, year

#### Evidence synthesis

The results of the quantitative studies are presented in Appendix 6 (Table A-9) and the risk of bias assessments are presented in Table 14.

##### NIMHD framework: individual level – biological domain

Within the individual level and biological domain, the following factors were identified: maternal BMI,^22,28,31,34,37,42,45,57^ gestational age,^28,34,40,43,67^ postpartum depression,^22,34,36,43,68^ mode of delivery,^22,28,34,40,61^ diabetes,^29,55^ hypertension,^45^ and gestational weight gain.^34^ The following factors had enough evidence to assess the evidence: maternal BMI,^22,28,31,34,37,42,45,57^ gestational age,^28,34,40,43,67^ postpartum depression,^22,34,36,43,68^ and mode of delivery.^22,28,34,40,61^ The following factors did not have enough evidence to synthesize and draw a summary statement: diabetes and gestational diabetes,^29,55^ hypertension,^45^ and gestational weight gain.^34^

###### Maternal BMI/pre-pregnancy obesity

Maternal BMI was examined in six studies (eight articles^22,28,31,34,37,42,45,57^: three PCS,^34,42,45^ five cross-sectional),^22,28,31,37,57^ five (six articles) of which examined human milk feeding initiation,^28,31,34,37,42,57^ and three (four articles) of which examined any and exclusive human milk feeding duration,^22,31,37,45^ assessed categorically between 6 weeks to 6 months. One study also examined meeting intention to breastfeed for 6 months as an outcome, which is described with human milk feeding duration.^45^

Maternal BMI, including pre-pregnancy BMI (five articles)^28,31,37,42,57^ and postpartum BMI, (one article)^34^ and human milk feeding initiation was examined in five studies (six articles),^28,31,34,37,42,57^ two of which examined moderation by interaction,^34,37^ four of which examined moderation by stratifying by race and ethnicity,^28,37,42,57^ and one of which stratified by pre-pregnancy BMI and SES (income and education).^31^ The two studies that examined moderation by interactions^34,37^ had mixed findings, with one study reporting a null interaction with race (Black versus White/other mothers) and postpartum BMI at 6 weeks,^34^ and another study reporting a significant interaction between race (Black versus White) and pre-pregnancy BMI on human milk feeding initiation, which was further explored by stratifying by race.^37^ When stratified by race, there were significantly lower odds of initiation for pre-pregnancy BMI ≥ 35 (but not significant for BMI <18.5, BMI 25-29.9, and BMI 30-34.9) compared to a pre-pregnancy BMI of 18.5-25 for White mothers; however, this relationship was not significant for Black mothers. Among the studies that stratified by race and ethnicity, most reported that pre-pregnancy obesity (versus normal BMI) was not associated with human milk feeding initiation among Black mothers,^28,42,57^ whereas pre-pregnancy obesity (versus normal BMI) was associated with lower odds of initiation among White mothers.^28,37,42^ Among Hispanic mothers, two studies^28,57^ reported significantly lower initiation with pre-pregnancy obesity (versus normal BMI), and one study^42^ reported null findings for pre-pregnancy obesity (versus normal BMI). Overweight (versus normal) pre-pregnancy BMI for Black, White, and Hispanic mothers was consistently not associated with initiation.^28,42,57^ Underweight pre-pregnancy BMI was consistently not associated with initiation among Black and White mothers.^28,42,57^ Among Hispanic mothers, underweight (versus normal) pre-pregnancy BMI was not associated with initiation in two studies,^28,42^ while one study reported significantly lower initiation with underweight (versus normal) pre-pregnancy BMI.^57^ Finally, the study that stratified by pre-pregnancy BMI and SES did not have clear trends.^31^ In summary, although the two studies on moderation by interaction were mixed for pre-pregnancy BMI or postpartum BMI, combined with the analyses that stratified by race and ethnicity, the evidence suggests that pre-pregnancy BMI may moderate the relationship between race and human milk feeding initiation among White and Black mothers.

Maternal BMI, specifically pre-pregnancy BMI, and any or exclusive human milk feeding duration, assessed categorically between 6 weeks to 6 months, was examined in four studies,^22,31,37,45^ one of which examined mediation,^45^ two of which examined moderation by interaction,^22,37^ one of which stratified by race and ethnicity,^37^ and one of which stratified by pre-pregnancy BMI and SES (income and education).^31^ The mediation study reported that pre-pregnancy obesity (higher in Black mothers) mediated the relationship between race (Black versus White) and breastfeeding to 6 months or meeting intention to breastfeed to 6 months.^45^ However, this was null for exclusive breastfeeding at 6 weeks.^45^ The two studies on moderation via interaction had mixed findings,^22,37^ with one study reporting a null interaction (White, Native Hawaiian, Samoan, Filipino, Japanese, Chinese, Korean, Black, Other/unknown)^22^ and another study reporting a significant interaction (Black, White),^37^ which was explored further by stratifying by race. When stratified by race, the study reported a higher hazard of discontinuing breastfeeding with BMI 25-29.9 and ≥35 (versus normal BMI) for White mothers, but not for Black mothers.^37^ Finally, the study that stratified by pre-pregnancy BMI and SES did not have clear trends.^31^ In general, studies varied in significance across analyses (mediation, moderation) and by the human milk feeding duration outcome.

The evidence was assessed using the following domains:

- [underlined: Consistency]: Consistency varied between breastfeeding initiation and duration, with more consistency in statistical significance for initiation, possibly due to larger sample sizes, than duration. For initiation, the moderation by interaction studies were mixed for White and Black mothers, but analyses stratified by race had consistent direction of associations and significance between Black and White mothers, suggesting moderation. For duration, studies were not consistent in significance when examining Black versus White mothers, with a small number of studies/analyses reporting both significant and null results for mediation or moderation.
- [underlined: Precision]: Study effect estimates and confidence intervals were not examined for this rapid review. Sample sizes for maternal BMI ranged from n=205 to n=1,161,949, with larger studies tending to examine human milk feeding initiation.
- [underlined: Risk of bias]: There is a concern for risk of bias due to confounding for all observational studies. However, risk of bias due to confounding was not formally examined for this rapid review question because a discrete list of key confounders could not be identified a priori due to the exploratory nature of the rapid review. All studies had low risk of bias for selection of participants into the study and deviations from intended exposures. Most studies had moderate risk of bias for outcome measurement, and all studies had moderate risk of bias for selection of reported results. Approximately half of studies had serious risk of bias for classification of exposures due to self-report of maternal BMI, while the remaining studies had primarily low risk of bias, and one had moderate risk of bias. Approximately half of studies had low risk of bias for missing data, while the remaining studies had primarily moderate risk of bias, and one study had serious risk of bias.
- [underlined: Directness]: All studies aligned with the population, exposure, comparator, and outcomes in the analytic framework. Most studies for human milk feeding initiation and half of studies for human milk feeding duration conducted analyses of maternal BMI stratified by race and ethnicity or analyses stratified by maternal BMI, which may be less direct than assessing moderation by testing interactions.
- [underlined: Generalizability]: The evidence is generalizable to the United States population.

Summary statement: Evidence suggests that pre-pregnancy obesity, compared to a normal pre-pregnancy BMI, may be associated with lower human milk feeding initiation among White, but not Black, mothers. There is not enough consistent evidence to determine whether maternal BMI is associated with racial and ethnic disparities in human milk feeding duration.

###### Postpartum depression

Postpartum depression was examined in five studies^22,34,36,43,68^ (three PCS,^34,36,43^ two cross-sectional)^22,68^ one of which examined human milk feeding initiation^34^ and four of which examined any or exclusive human milk feeding duration,^22,36,43,68^ assessed continuously or categorically between 8 weeks to 8 months.

Postpartum depression and human milk feeding initiation was examined in one study, reporting that postpartum depression did not interact with race (Black versus White/Other) to impact breastfeeding initiation.^34^ There was not enough evidence to assess the evidence and draw a summary statement.

Postpartum depression, including depression symptomology, and any and exclusive human milk feeding duration, assessed continuously or categorically between 8 weeks to 8 months, was examined in four studies.^22,36,43,68^ One examined mediation,^43^ two examined moderation by interaction,^22,36^ and one examined moderation by stratifying by race and ethnicity.^68^ All analyses were non-significant except for the study that stratified by race and ethnicity: Mothers with postpartum depression, compared to mothers without postpartum depression, had significantly lower exclusive breastfeeding rates at 3 months among Black and White mothers, but this was not significant for Asian, Hispanic, and Other mothers in analyses stratified by race and ethnicity.^68^ The studies reporting non-significant mediation and moderation by interaction analyses compared Black to White mothers^22,36,43^ and Hispanic to White or Black mothers.^36,43^ In general, postpartum depression did not mediate or moderate the association between race and ethnicity for Black, White, and Hispanic mothers and human milk feeding duration.

Although there were not enough studies for postpartum depression and human milk feeding initiation, the evidence for postpartum depression and human milk feeding duration was assessed using the following domains:

- [underlined: Consistency]: The results of the analyses were predominantly non-significant among mothers of all races and ethnicities (Black, White, and Hispanic).
- [underlined: Precision]: Study effect estimates and confidence intervals were not examined for these studies. For postpartum depression, sample sizes ranged from n=450 to n=44,294.
- [underlined: Risk of bias]: There is a concern for risk of bias due to confounding for all observational studies. However, risk of bias due to confounding was not formally examined for this rapid review question because a discrete list of key confounders could not be identified a priori due to the exploratory nature of the rapid review. A majority of studies had low risk of bias for selection of participants into the study, classification of exposures, and deviations from intended exposures. All studies had moderate risk of bias for measures of outcomes and selection of reported results. One study had a serious risk of bias for missing data due to excluded participants’ characteristics being associated with the breastfeeding outcome, while two studies had moderate risk of bias and two studies had low risk of bias for this domain.
- [underlined: Directness]: All studies aligned with the population, exposure, comparator, and outcomes in the analytic framework.
- [underlined: Generalizability]: The evidence is generalizable to the United States population.

Summary statement: Evidence suggests that postpartum depression may not be associated with the relationship between race and ethnicity in human milk feeding duration among Black, Hispanic, and White mothers.

###### Mode of delivery

Mode of delivery was examined in five articles^22,28,34,40,61^ (one PCS,^34^ four cross-sectional),^22,28,40,61^ four of which examined human milk feeding initiation,^28,34,40,61^ and one of which examined exclusive breastfeeding at 8 weeks.^22^

Mode of delivery and human milk feeding initiation was examined in three studies (four articles),^28,34,40,61^ two of which examined moderation by interaction,^34,61^ and two of which examined moderation by stratifying by race and ethnicity.^28,40^ Both studies that examined moderation by interaction reported non-significant interactions between delivery mode (delivery type in one study; repeated cesarean section versus vaginal birth after cesarean section) and race on human milk feeding initiation.^34,61^ One study compared between Black and White/other mothers,^34^ and another study compared Black, Hispanic, and other non-Hispanic mothers to White mothers.^61^ Two studies that stratified by race (Black and White in both studies) reported inconsistent significance and directionality within mothers of each race.^28,40^ Among Black mothers, one study found a null association,^28^ while another study found higher odds of initiation with cesarean (versus vaginal) delivery.^40^ Among White mothers, one study detected significantly lower odds of initiation for cesarean (versus vaginal) delivery,^28^ while the second study did not detect a significant association.^40^ Due to inconsistent results, a summary statement was not drawn for mode of delivery and human milk feeding initiation.

Mode of delivery and exclusive human milk feeding at 8 weeks was examined in one study,^22^ and therefore, there were too few studies to assess the evidence and draw a summary statement for mode of delivery and human milk feeding duration.

Although there were not enough studies for mode of delivery and human milk feeding duration, the evidence for mode of delivery and human milk feeding initiation was assessed using the following domains:

- [underlined: Consistency]: Studies were relatively inconsistent in significance and the directionality of significant associations for human milk feeding initiation for Black and White mothers.
- [underlined: Precision]: Study effect estimates and confidence intervals were not examined for this rapid review. Sample sizes ranged from n=450 to n=501,967, with the majority including fewer than 9,000 participants.
- [underlined: Risk of bias]: There is a concern for risk of bias due to confounding for all observational studies. However, risk of bias due to confounding was not formally examined for this rapid review question because a discrete list of key confounders could not be identified a priori due to the exploratory nature of the rapid review. All studies had low risk of bias for selection of participants into the study, classification of exposures, and deviations from intended exposures. The majority of studies had moderate risk of bias for measures of outcomes due to self-report of human milk feeding and for selection of reported results. Two studies had low risk of bias for missing data, one had moderate, one had no information, and one study with significant findings had serious risk of bias due to high rates of missing data that differed by race. One study, also with significant findings, had a serious risk of bias for selection of reported results due to inconsistent reporting of significant factors.
- [underlined: Directness]: All studies aligned with the population, exposure, comparator, and outcomes in the analytic framework. Half of the studies for human milk feeding initiation conducted analyses of mode of delivery stratified by race and ethnicity, which may be less direct than assessing moderation by testing interactions.
- [underlined: Generalizability]: The evidence is generalizable to the United States population.

Summary statement: There is not enough consistent evidence among the small number of studies to determine whether mode of delivery is associated with racial and ethnic disparities in human milk feeding initiation.

###### Gestational age

Gestational age was examined in five studies^28,34,40,43,67^ (two PCS,^34,43^ three cross-sectional),^28,40,67^ all of which examined human milk feeding initiation,^28,34,40,43,67^ and one of which examined mean human milk feeding duration.^43^

Gestational age and human milk feeding initiation was examined in five studies,^28,34,40,43,67^ one of which examined mediation,^43^ one of which examined moderation by interaction,^34^ two of which stratified by race and ethnicity,^28,40^ and one of which stratified by the gestational age and race and ethnicity.^67^ The one study on mediation^43^ and the one study on moderation by interaction^34^ did not detect significant mediation (Black versus White versus Hispanic in separate analyses) or moderation (Black, White/other) of the relationship between race and ethnicity and human milk feeding initiation. The two studies that stratified by race and ethnicity reported significant associations between gestational age and human milk feeding initiation among Black,^28,40^ Hispanic,^28^ and White^28,40^ mothers. Among Black mothers, the two studies reported different directionalities: one study reported higher initiation with preterm (versus full term) delivery^40^ while the other study reported lower odds of initiation with preterm (versus term) delivery.^28^ Among Hispanic mothers, one study reported lower odds of initiation with birth at 34-36 weeks gestation compared to term birth.^28^ Among White mothers, one study reported lower odds of initiation for 34-36 weeks gestation compared to term birth, but not for 28-31 weeks, and 32-33 weeks gestation compared to term birth.^28^ The second study on White mothers did not retain preterm birth as a variable in the model.^40^ Finally, there was no clear direction of results in the study that stratified by income, marital status, and preterm birth for non-Hispanic Black, non-Hispanic White, and Hispanic mothers.^67^ In general, gestational age was not a significant mediator or moderator of the association between race (Black, White) and human milk feeding initiation.

Gestational age and mean human milk feeding duration was examined in one article,^43^ and therefore, there were too few studies to assess the evidence and draw a summary statement for gestational age and human milk feeding duration.

Although there were not enough studies for gestational age and human milk feeding duration, the evidence for gestational age and human milk feeding initiation was assessed using the following domains:

- [underlined: Consistency]: Overall, there was some inconsistency in significance and in directionality in the impact of gestational age between mothers of different races and ethnicities. Studies that examined mediation or moderation by interaction had consistently null findings. Studies that stratified by race and ethnicity reported significant findings between gestational age and human milk feeding initiation, with the directionality of results differing by race: Black mothers had mixed findings, while Hispanic and White mothers had lower odds of initiation with preterm compared to term births.
- [underlined: Precision]: Study effect estimates and confidence intervals were not examined for these studies. Sample sizes ranged from n=450 to n=501,967.
- [underlined: Risk of bias]: There is a concern for risk of bias due to confounding for all observational studies. However, risk of bias due to confounding was not formally examined for this rapid review question because a discrete list of key confounders could not be identified a priori due to the exploratory nature of the rapid review. All studies had low risk of bias for selection of participants into the study, classification of exposures, deviations from intended exposures. Most of the studies had moderate risk of bias for measurement of outcomes and selection of reported results. One had a low risk of bias for measurement of outcomes, and one study had a serious risk of bias for selection of reported results due to inconsistent reporting of significant factors. For risk of bias due to missing data, two studies had low risk of bias, one had moderate risk of bias, one had serious risk of bias, and one had no information.
- [underlined: Directness]: All studies aligned with the population, exposure, comparator, and outcomes in the analytic framework. More than half of studies for human milk feeding initiation conducted analyses of the gestational age stratified by race and ethnicity, which may be less direct than assessing moderation by testing interactions.
- [underlined: Generalizability]: The evidence is generalizable to the United States population.

Summary statement: Evidence suggests that gestational age may not be associated with the relationship between race and ethnicity (Black, Hispanic, White) and human milk feeding initiation.

##### NIMHD framework: individual level – behavioral domain

Within the individual level and behavioral domain, the following factors were identified: smoking,^7,10,13,25,34,36,40,43,56,63^ attitudes and beliefs,^43,50^ intention to breastfeed,^36,45^ having a breastfeeding plan,^23^ perceived control,^50^ information^50^ or knowledge of breastfeeding recommendation,^62^ early feeding practices,^24^ total stress factors,^40^ and substance use (other than smoking) during pregnancy.^10^ The following factor had enough evidence to assess the evidence: smoking.^7,10,13,25,34,36,40,43,56,63^ The following factors did not have enough evidence to synthesize and draw a summary statement: attitudes and beliefs,^43,50^ intention to breastfeed,^36,45^ having a breastfeeding plan,^23^ perceived control,^50^ source of infant care information^50^ or knowledge of breastfeeding recommendation,^62^ early feeding practices,^24^ total stress factors,^40^ and substance use (other than smoking) during pregnancy.^10^

###### Smoking

Smoking, including nicotine use, was examined in 10 articles^7,10,13,25,34,36,40,43,56,63^ (4 PCS,^7,34,36,43^ 5 cross-sectional,^13,25,40,56,63^ 1 RCS),^10^ 8 of which examined human milk feeding initiation^7,10,13,25,34,36,40,63^ and 4 of which examined human milk feeding duration.^25,36,43,56^ Human milk feeding duration was assessed continuously and categorically, assessed between 12 weeks and 8 months.^25,36,43,56^

Smoking and human milk feeding initiation was examined in eight studies,^7,10,13,25,34,36,40,63^ five of which examined moderation by interaction,^7,13,34,36,63^ two by stratifying by race and ethnicity,^25,40^ and one by stratifying by type of substance use.^10^ All five studies that tested interactions reported that smoking during pregnancy, current smoking, or postpartum smoking did not moderate the relationship between race and ethnicity (Black, White, Hispanic or Other) and human milk feeding initiation.^7,13,34,36,63^ In the two studies that stratified by race and ethnicity, smoking status, including lifetime smoking or current smoking status, was not associated with human milk feeding initiation across all racial and ethnic groups examined (Black mothers in two studies,^25,40^ White mothers in one study,^40^ and Mexican mothers in one study).^25^ One RCS conducted analyses stratified by type of substance used (including nicotine) and reported significantly lower exclusive breastfeeding at the hospital and discharge for Asian/Hawaiian Native or Pacific Islander, Hispanic, and multirace/other mothers with nicotine use compared to White mothers with nicotine use, but this was not significant for American Indian/Alaska Native, and Black or African American mothers compared to White mothers.^10^ In general, smoking was not a significant mediator or moderator of the association between race and ethnicity (Black, White, Hispanic) and human milk feeding initiation.

Smoking and any and exclusive human milk feeding duration, assessed continuously and categorically between 12 weeks to 8 months, was examined in four studies.^25,36,43,56^ One study tested mediation,^43^ two examined moderation by interaction,^36,56^ and two stratified their analyses by race and ethnicity.^25,56^ The mediation analysis found that smoking at 1 month postpartum did not mediate the association between race and ethnicity (Black, Hispanic, White) and mean breastfeeding duration.^43^ Among the two studies that tested interactions,^36,56^ one study reported a significant interaction between postpartum smoking and race and ethnicity (Hispanic, non-Hispanic Black, non-Hispanic White, others) for exclusive breastfeeding at or longer than 12 weeks,^56^ while another study reported a non-significant interaction between smoking after birth and race and ethnicity (foreign-born Black and native-born Black, Puerto Rican, other Hispanic, non-Hispanic White) on breastfeeding duration up to 8 months.^36^ Among the two studies that stratified by race and ethnicity,^25,56^ one study found lower odds of exclusive breastfeeding ≥12 weeks with postpartum smoking, compared to no smoking, among Black, White, and other mothers,^56^ while another study found null associations between lifetime smoking and breastfeeding for at least 6 months among Mexican and non-Hispanic Black mothers.^25^ In general, smoking was not a significant mediator or moderator of the association between race and ethnicity (Black, Hispanic, White) and human milk feeding duration.

The evidence was assessed using the following domains:

- [underlined: Consistency]: The studies were consistent in that most reported that smoking did not mediate or moderate the relationship between race and ethnicity and human milk feeding outcomes.
- [underlined: Precision]: Study effect estimates and confidence intervals were not examined for these studies. Sample sizes for smoking ranged from n=247 to n=84,742.
- [underlined: Risk of bias]: There is a concern for risk of bias due to confounding for all observational studies. However, risk of bias due to confounding was not formally examined for this rapid review question because a discrete list of key confounders could not be identified a priori due to the exploratory nature of the rapid review. All studies had low risk of bias for selection of participants into the study. The majority of studies had low risk of bias for classification of exposures and deviations from intended exposures. Most studies had moderate risk of bias for measures of the outcome and selection of reported results. One study had a serious risk of bias for selection of reported results due to inconsistent reporting of results depending on the outcome.
- [underlined: Directness]: All studies aligned with the population, exposure, comparator, and outcomes in the analytic framework. Half of the studies that examined human milk feeding duration conducted analyses of smoking stratified by race and ethnicity, which may be less direct than assessing moderation by testing interactions.
- [underlined: Generalizability]: The evidence is generalizable to the United States population.

Summary statement: Evidence indicates that smoking is not associated with racial and ethnic disparities in human milk feeding initiation among Black, Hispanic, and White mothers. Evidence suggests that postpartum smoking may not be associated with racial and ethnic disparities in human milk feeding durations among Black, Hispanic, and White mothers.

##### NIMHD framework: individual level – sociocultural environment domain

Within the individual level and sociocultural environment, the following factors were identified: nativity and acculturation,^1,12,18,21,25,36,70^ maternal age,^13,28,34,36,40,43,50,52^ maternal education,^7,13,18,25,28,30,31,34,36,40,43,45,50^ income and income-related factors,^30,31,36,40,43,45,48,67^ and parity,^4,13,27,28,34,36,40,43,50^ all of which had enough evidence to assess the evidence.

###### Nativity and acculturation

Maternal nativity and acculturation was examined in seven studies^1,12,18,21,25,36,70^ (two PCS,^1,9,18,21,25,36,70^ four cross-sectional,^18,36^ one RCS),^12^ six of which examined human milk feeding initiation,^1,9,18,21,25,36,70^ and two of which examined any and exclusive human milk feeding duration, assessed categorically between 6 to 8 months.

Maternal nativity and acculturation and human milk feeding initiation, including breastfeeding for 1 week, was examined in six studies,^1,18,21,25,36,70^ two of which examined moderation by interaction,^18,36^ four of which examined moderation by stratifying for race and ethnicity,^18,21,25,36^ and two of which incorporated nativity into a variable with race and ethnicity.^1,70^ Both studies that tested interactions reported significant interactions between nativity and race and ethnicity (Black, Other, White in one study,^18^ and Foreign-born Black, Non-Hispanic native-born Black, Other Hispanic, Puerto Rican versus Non-Hispanic White in another study)^36^ on human milk feeding initiation, both of which further explored by stratifying by race and ethnicity. When stratified by race and ethnicity, both studies reported that foreign-born Black mothers had higher initiation for different comparators: one compared to U.S.-born Black mothers^18^ and another compared to non-Hispanic White mothers.^36^ However, this was null for native-born Black mothers compared to non-Hispanic White mothers,^36^ and foreign-born White or other mothers compared to U.S.-born White or other mothers, respectively.^18^ Among the other two studies that stratified by race and ethnicity,^21,25^ one study reported significantly higher odds of breastfeeding initiation for foreign-born English-speaking mothers than U.S.-born mothers among all races and ethnicities, including Black, Hispanic, Asian/Pacific Islander, Other, and White mothers; another study reported significantly higher initiation with low acculturation among Mexican mothers but not among Puerto Rican mothers.^25^ Both studies that stratified by maternal nativity or acculturation reported significant findings^1,70^ with higher initiation among non-U.S.-born Arab Americans^1^ (versus U.S.-born Arab American), non-U.S.-born White mothers (versus U.S.-born Arab American),^1^ and among immigrant Hispanic parents and immigrant other race and ethnicity parents compared to U.S.-born non-Hispanic White parents and U.S.-born child.^70^ Taken together, studies suggest that nativity moderated the association between race and ethnicity and human milk feeding initiation, with higher initiation among foreign-born mothers compared to U.S.-born mothers who were Black, while associations were less consistent for White mothers.

Maternal nativity and human milk feeding duration, assessed categorically between 6 and 8 months, was examined in two studies,^12,36^ one of which examined moderation by interaction,^36^ and one of which compared foreign-born White to U.S.-born White mothers.^12^ Due to the small number of studies examining nativity, findings were not synthesized and the evidence was not assessed.

Although there were not enough studies for maternal nativity and human milk feeding duration, the evidence for maternal nativity and human milk feeding initiation was assessed using the following domains:

- [underlined: Consistency]: Studies on maternal nativity and human milk feeding initiation were somewhat consistent in significance and in directionality, with greater human milk feeding initiation rates among non-U.S. born mothers; this was most consistent for Black mothers.
- [underlined: Precision]: Study effect estimates and confidence intervals were not examined for these studies. Sample size for maternal nativity ranged from n=1,140 to n=1,067,375.
- [underlined: Risk of bias]: There is a concern for risk of bias due to confounding for all observational studies. However, risk of bias due to confounding was not formally examined for this rapid review question because a discrete list of key confounders could not be identified a priori due to the exploratory nature of the rapid review. Risk of bias was low for all studies for selection of participants into the study, and classification of exposures. A majority of studies had low risk of bias for deviations from intended exposures. Half of the studies had low risk of bias for missing data and measurement of outcomes, and approximately half had moderate risk of bias for these domains. Risk of bias was moderate for all studies for selection of reported results.
- [underlined: Directness]: All studies aligned with the population, exposure, comparator, and outcomes in the analytic framework. More than half of studies for human milk feeding initiation conducted analyses of maternal nativity stratified by race and ethnicity or stratified by maternal nativity, which may be less direct than assessing moderation by testing interactions.
- [underlined: Generalizability]: The evidence is generalizable to the United States population.

Summary statement: Evidence suggests that maternal nativity may be associated with the relationship between race and human milk feeding initiation among Black and White mothers, such that foreign-born Black mothers initiated human milk feeding at higher rates than U.S.-born Black mothers, while associations were inconsistent for White mothers.

###### Maternal age

Maternal age was examined in eight studies^13,28,34,36,40,43,50,52^ (five PCS,^34,36,43,50,52^ three cross-sectional),^13,28,40^ six of which examined human milk feeding initiation,^13,28,34,40,43,52^ and four of which examined any and exclusive human milk feeding duration,^36,43,50,52^ assessed continuously and categorically between 2 and 8 months.

Maternal age and human milk feeding initiation was examined in six studies,^13,28,34,40,43,52^ one of which examined mediation,^43^ three of which examined moderation by interaction,^13,34,52^ and two of which examined moderation by stratifying by race and ethnicity.^28,40^ The one study on mediation (Black versus White; Hispanic versus White; Hispanic versus Black)^43^ and all three studies on moderation by interaction (Black, other, White),^13,34,52^ reported null associations, including when examining mothers with education less than 12 years.^40^ In the two articles that stratified by race and ethnicity, both reported significantly higher odds of initiation in older mothers compared to younger mothers among White mothers, but not among Black mothers.^28,40^ In general, maternal age was not a significant mediator or moderator of the association between race and ethnicity (Black, White, Hispanic) and human milk feeding initiation.

Maternal age and any and exclusive human milk feeding duration, assessed continuously and categorically between 2 and 8 months, was examined in four studies,^36,43,50,52^ two of which examined mediation^43,50^ and two of which examined moderation by interaction.^36,52^ When comparing Black versus White mothers, one study reported that maternal age did not mediate the relationship between race and initiation,^43^ and the second study reported that maternal age greater than or equal to 25 years (lower in U.S.-born Black mothers) mediated any breastfeeding at 2-6 months, which was lower in U.S.-born Black mothers.^50^ One of these studies also compared Hispanic (Spanish- or English-speaking) to White and Black mothers in separate analyses and reported null mediation by maternal age,^43^ while one of these studies also compared foreign-born Black to U.S.-born White mothers and reported that maternal age was not a significant mediator.^50^ Both studies on moderation by interaction reported that maternal age did not significantly interact with race and ethnicity (Black, Hispanic, White mothers) to impact human milk feeding duration.^36,52^ In general, maternal age was not a significant mediator or moderator of the association between race and ethnicity (Black, White, Hispanic) and human milk feeding duration.

The evidence was assessed using the following domains:

- [underlined: Consistency]: The studies on maternal age were relatively consistent, with most suggesting that maternal age did not mediate or moderate the relationship between race and ethnicity and human milk feeding initiation or duration of any or exclusive human milk feeding.
- [underlined: Precision]: Study effect estimates and confidence intervals were not examined for these studies. Sample sizes for maternal age ranged from n=225 to n=501,967.
- [underlined: Risk of bias]: There is a concern for risk of bias due to confounding for all observational studies. However, risk of bias due to confounding was not formally examined for this rapid review question because a discrete list of key confounders could not be identified a priori due to the exploratory nature of the rapid review. The majority of studies had low risk of bias for selection of participants into the study, classification of exposures, and deviations from intended exposures. The majority of studies had moderate risk of bias for measures of outcomes and selection of reported results. One study had serious risk of bias for selection of reported results due to inconsistent reporting of results depending on the outcome. Approximately half of studies had low and half had moderate risk of bias for missing data; one study had serious risk of bias for missing data due to high rates of missing data that differed by race.
- [underlined: Directness]: All studies aligned with the population, exposure, comparator, and outcomes in the analytic framework.
- [underlined: Generalizability]: The evidence is generalizable to the United States population.

Summary statement: Evidence suggests that maternal age may not be associated with racial and ethnic disparities in human milk feeding initiation or duration.

###### Maternal education

Maternal education was examined in 13 studies^7,13,18,25,28,30,31,34,36,40,43,45,50^ (7 PCS,^7,18,34,36,43,45,50^ 6 cross-sectional),^13,25,28,30,31,40^ ^11^ of which examined human milk feeding initiation,^7,13,18,25,28,30,31,34,36,40,43^ and 5 of which examined any and exclusive duration of human milk feeding,^25,31,43,45,50^ including 1 study that examined meeting intention to breastfeed for 6 months as an outcome, which are described with human milk feeding duration.^45^ One study examined SES as the factor, a composite of income and education, and was included in both income and education sections.^31^

Maternal education and human milk feeding initiation was examined in 11 studies,^7,13,18,25,28,30,31,34,36,40,43^ 1 of which examined mediation,^43^ 6 of which examined moderation by interaction,^7,13,18,30,34,36^ 3 of which examined moderation by stratifying for race and ethnicity,^25,28,40^ and one of which examined moderation by stratifying by maternal education.^31^ The one mediation study^43^ reported that maternal education significantly mediated differences in initiation between Black and White women, but not between Hispanic and Black or between Hispanic and White women. Six studies examined moderation by interaction, all of which reported null interactions between maternal education and race and ethnicity on initiation among Black, Hispanic, White and Other mothers.^7,13,18,30,34,36^ Three studies examined the association between education and human milk feeding initiation stratified by race and ethnicity and reported significantly higher odds of initiation with increasing education among all racial and ethnic groups examined (primarily Black, Hispanic, and White mothers),^25,28,40^ except for Mexican mothers in one study.^25^ In general, maternal education did not impact the association between race and ethnicity and human milk feeding initiation for Black, Hispanic, and White mothers.

Maternal education and any and exclusive human milk feeding duration, assessed continuously and categorically between 6 weeks to 6 months, was examined in five studies^25,32,43,45,50^; three examined mediation,^43,45,50^ one stratified by race and ethnicity,^25^ and one stratified by pre-pregnancy BMI and SES.^31^ One study assessed meeting intention to breastfeed for 6 months.^45^ All three studies reported that education mediated the association between race between Black and White women and human milk feeding duration, with college education lower in Black mothers and shorter human milk feeding duration among Black mothers.^43,45,50^ However, one of these studies also compared foreign-born Black mothers to U.S.-born White mothers and reported that education (lower in Foreign-born Black mothers) mediated breastfeeding duration (higher in Foreign-born Black mothers), which was opposite in directionality compared to U.S.-born Black versus U.S.-born White mothers.^50^ Only one of these three articles compared Spanish-speaking or English-speaking Hispanic to White or to Black mothers (four comparisons), three of which did not detect mediation by maternal education and one which detected significant mediation when comparing English-speaking Hispanic (lower college education, lower mean breastfeeding duration) to White mothers.^43^ The one study that stratified by race and ethnicity reported null associations between education and breastfeeding for at least 6 months among Mexican and non-Hispanic Black mothers.^25^ The one study on meeting intention to breastfeed for 6 months reported that education did not mediate difference between Black and White mothers.^45^ The one study that stratified by pre-pregnancy BMI and by SES (income and education) was difficult to interpret.^31^ In general, education significantly mediated the relationship between race (Black versus White) and human milk feeding duration.

The evidence was assessed using the following domains:

- [underlined: Consistency]: Studies examining mediation or moderation by maternal education were consistent, with most studies reporting that education did not mediate or moderate the relationship between race and human milk feeding initiation, and most studies reporting that maternal education significantly mediated differences in any or exclusive human milk feeding duration between Black and White mothers.
- [underlined: Precision]: Study effect estimates and confidence intervals were not examined for these studies. The sample size for education ranged from n=205 to n=501,967. The majority of the sample sizes for studies examining education were less than n=7,000.
- [underlined: Risk of bias]: There is a concern for risk of bias due to confounding for all observational studies. However, risk of bias due to confounding was not formally examined for this rapid review question because a discrete list of key confounders could not be identified a priori due to the exploratory nature of the rapid review. The majority of studies had low risk of bias for selection of participants into the study, classification of exposures, and deviations from intended exposures. However, the majority of studies had moderate risk of bias for measures of outcomes and selection of reported results. Approximately half of studies had low risk of bias and half had moderate risk of bias for missing data. One study had a serious risk of bias on missing data due to high rates of missing data on race. One study had a serious risk of bias for selection of reported result due to inconsistent reporting of results depending on the outcome.
- [underlined: Directness]: All studies aligned with the population, exposure, comparator, and outcomes in the analytic framework.
- [underlined: Generalizability]: The evidence is generalizable to the United States population, including populations with low-income.

Summary statement: Evidence indicates that maternal education is not associated with racial and ethnic disparities in human milk feeding initiation among Black, Hispanic, and White mothers. Evidence suggests that lower levels of maternal education may be associated with shorter human milk feeding duration for Black mothers compared to White mothers.

###### Income and income-related factors

Income and income-related factors were examined in eight articles^30,31,36,40,43,45,48,67^ (three PCS,^36,43,45^ five cross-sectional),^30,31,40,48,67^ seven of which examined human milk feeding initiation,^30,31,36,40,43,48,67^ and six of which examined any and exclusive human milk feeding duration,^31,36,43,45,48,64^ assessed continuously and categorically between 6 weeks to 8 months. Income was examined in five studies^30,36,43,45,67^; other factors related to income that were examined included SES,^31^ participation in welfare 12 months before pregnancy or after birth,^36^ unpaid bills prior to pregnancy,^40^ and food security.^48^ One article examined meeting goals to breastfeed for 6 months as an outcome, which is described with human milk feeding duration.^45^

Income, including income-related factors, and human milk feeding initiation was examined in seven studies,^30,31,36,40,43,48,67^ four of which examined income,^30,36,43,67^ while one study each examined SES (education and income combined),^31^ welfare receipt 12 months before pregnancy or after birth,^36^ unpaid bills prior to pregnancy,^40^ and food security.^48^ One study on income tested mediation^43^; two studies tested moderation by interaction,^30,36^ one of which assessed income,^30^ while a second assessed material assets and participation in welfare 12 months before pregnancy.^36^ Three studies stratified by race and ethnicity,^40,48,67^ one each examining income,^67^ food security,^48^ and unpaid bills prior to pregnancy.^40^ Two studies stratified by two or more factors: one stratified by pre-pregnancy BMI and SES^31^ and one stratified by income, marital status and gestational age.^67^ When examining the four studies that assessed income,^30,36,43,67^ the mediation analyses comparing Hispanic to White or Hispanic to Black mothers,^43^ the two interaction studies (both comparing Black, other, White),^30,36^ and the analyses stratifying by race and ethnicity (Black, Hispanic, White)^67^ were all null. However, the mediation analysis comparing Black to White mothers was significant.^43^ When examining other income-related factors, all findings were null, including welfare receipt 12 months before pregnancy for Black, Puerto Rican, other Hispanic, and White mothers,^36^ unpaid bills prior to pregnancy among Black and White mothers,^40^ and food security among Black, Hispanic, and White mothers.^48^ The two studies that stratified by two or more factors were difficult to interpret. Taken together, income, including income-related factors, did not appear to mediate or moderate the association between race and ethnicity (Black, Hispanic, White) and human milk feeding initiation.

Income, including income-related factors, and any and exclusive human milk feeding duration, assessed continuously and categorically between 6 weeks to 8 months, was examined in five studies,^31,36,43,45,48,64^ two of which examined income,^43,45^ and one study each which examined food security,^48^ welfare receipt after birth,^36^ and SES (education and income combined).^31^ Two studies on income tested mediation^43,45^; two studies examined moderation by interaction,^36,64^ one examining participation in welfare after birth,^36^ one study on food security stratified by race and ethnicity^48^; and one study stratified by pregnancy BMI and SES (income and education combined).^31^ Among the two studies on income,^43,45^ one study reported that income did not mediate the relationship between race (Black versus White mothers) and mean duration,^43^ while one study reported that income significantly mediated the relationship between race and ethnicity (Black versus White mothers, but not for Hispanic versus White or Black mothers) and exclusive breastfeeding at 6 weeks and breastfeeding at 6 months^45^; results were null when examining meeting intention to breastfeed for 6 months.^45^ The remaining income-related factors were null, including participation in welfare after birth for Black, Puerto Rican, other Hispanic, and White mothers,^36^ and food security for Black, Hispanic, and White mothers.^48^ The one study that stratified by pregnancy BMI and SES (income and education combined) was difficult to interpret due to results varying by racial comparisons (Hispanic versus White; Black versus White), SES level (low or middle), and pre-pregnancy BMI (normal or overweight/obese).^31^ Taken together, income, including income-related factors, generally did not mediate or moderate the association between race and ethnicity (Black, Hispanic, and White mothers) and any and exclusive human milk feeding duration.

The evidence was assessed using the following domains:

- [underlined: Consistency]: Studies were generally consistent, reporting primarily null findings for human milk feeding initiation and duration.
- [underlined: Precision]: Study effect estimates and confidence intervals were not examined. The sample size for income ranged from n=205 to n=6,859 overall. Sample sizes ranged from n=1,140 to n=6,859 for income and breastfeeding initiation and from n=205 to n=1,636 for income and any or exclusive human milk feeding duration.
- [underlined: Risk of bias]: There is a concern for risk of bias due to confounding for all observational studies. However, risk of bias due to confounding was not formally examined for this rapid review question because a discrete list of key confounders could not be identified a priori due to the exploratory nature of the rapid review. The majority of studies had low risk of bias for selection of participants into the study, classification of exposures, and deviations from intended exposures. One study had a serious risk of bias for classification of exposures due to self-report of pre-pregnancy BMI. The majority of studies had moderate risk of bias for measurement of the outcome, and selection of reported results. One study had serious risk of bias for selection of reported results due to inconsistent reporting of results depending on the outcome. Half of the studies had moderate risk of bias for missing data, three had low risk, and one had no information.
- [underlined: Directness]: All studies aligned with the population, exposure, comparator, and outcomes in the analytic framework. More than half of studies for human milk feeding initiation and the majority of studies for duration conducted analyses of the factor stratified by race and ethnicity, which may be less direct than assessing moderation by testing interactions.
- [underlined: Generalizability]: The evidence is generalizable to the United States.

Summary statement: Evidence suggests that income and income-related factors may not be associated with the relationship between race and ethnicity and human milk feeding initiation among Black, Hispanic, and White mothers. There is not enough consistent evidence to determine whether associations between race and ethnicity and human milk feeding duration vary by income and income-related factors.

###### Parity

Parity was examined in eight studies (nine articles^4,13,27,28,34,36,40,43,50^; six PCS,^4,27,34,36,43,50^ three cross-sectional)^13,28,40^ eight of which examined human milk feeding initiation,^4,13,27,28,34,40,43^ including one study that examined exclusive breastfeeding at discharge,^27^ and four of which examined any or exclusive human milk feeding duration.^4,36,43,50^

Parity, including one study that examined the number of children living with mother,^40^ and human milk feeding initiation, including exclusive breastfeeding at discharge,^27^ was examined in seven studies (eight articles).^4,13,27,28,34,40,43^ One article tested mediation,^43^ three examined moderation by interaction,^4,13,34^ and three stratified by race and ethnicity.^27,28,40^ The one mediation study^43^ and the three moderation by interaction studies^4,13,34^ reported null associations, all of which compared Black to White mothers,^4,13,34,43^ and three of which compared Hispanic to non-Hispanic,^13^ Black,^4,43^ and White^4,43^ mothers. Two of the three studies^27,28,40^ that stratified by race and ethnicity reported significant findings,^27,28^ and one reported null findings.^40^ One study reported null associations between number of children living with the mother and breastfeeding initiation among Black and White mothers^40^; one study reported significantly lower odds for multiparous compared to primiparous among mothers of all racial and ethnic groups, including Hispanic, Black, Other, and White mothers^29^; finally, one study reported significantly lower exclusive breastfeeding duration at discharge among nulliparous Black, Hispanic, and Asian mothers and multiparous Black, Hispanic, Asian and American Indian mothers, but not among nulliparous American Indian, Native Hawaiian/Pacific Islander mothers and multiparous Native Hawaiian/Pacific Islander mothers.^27^ Overall, the studies predominantly suggested that parity was not a significant mediator or moderator of the relationship between race and ethnicity (Black, Hispanic, and White mothers) and human milk feeding initiation.

Parity and any and exclusive human milk feeding duration, assessed continuously and categorically between 2 to 8 months, was examined in four studies.^4,36,43,50^ Two examined mediation^43,50^ and two examined moderation by interaction.^4,36^ None of the studies reported significant results, suggesting that parity and number of children did not mediate or moderate the association between race and ethnicity and any or exclusive breastfeeding duration among Black, Hispanic, and White women.

The evidence was assessed using the following domains:

- [underlined: Consistency]: Studies on parity and number of children for both human milk feeding initiation and any or exclusive duration were consistently null, with the majority of studies reporting null results for initiation, and all studies reporting null results for duration.
- [underlined: Precision]: Study effect estimates and confidence intervals were not examined. Sample sizes ranged from n=450 to n=501,967 for breastfeeding initiation and from n=1,140 to n=20,694 for any and exclusive breastfeeding duration.
- [underlined: Risk of bias]: There is a concern for risk of bias due to confounding for all observational studies. However, risk of bias due to confounding was not formally examined for this rapid review question because a discrete list of key confounders could not be identified a priori due to the exploratory nature of the rapid review. Risk of bias was low for selection of participants into the study, classification of exposures, and deviations from intended exposures. The majority of studies had moderate risk of bias for measurement of outcomes and selection of reported result. One study had a serious risk of bias on missing data due to high rate of missing data on race, while three studies had moderate risk, three studies had low risk, and one study had no information on missing data.
- [underlined: Directness]: All studies aligned with the population, exposure, comparator, and outcomes in the analytic framework.
- [underlined: Generalizability]: The evidence is generalizable to the United States population.

Summary statement: Evidence suggests that parity may not be associated with racial and ethnic disparities in human milk feeding initiation and duration among Black, Hispanic, and White mothers.

##### NIMHD framework: individual level – health care system domain

Within the individual level and health care system domain, the following factors were identified: insurance^28,40,44,45^ and contraception.^8^ Because only one study assessed contraception, there was not sufficient evidence to synthesize and a summary statement could not be drawn.^8^

###### Insurance

Insurance, including Medicaid coverage, was examined in four studies,^28,40,44,45^ (two PCS,^44,45^ two cross-sectional).^28,40^ Two studies examined human milk feeding initiation^28,40^ and two studies examined any and exclusive human milk feeding duration,^44,45^ assessed categorically between 6 weeks to 6 months. One study also examined meeting intention to breastfeed for 6 months as an outcome, which is described with human milk feeding duration.^45^

Insurance and human milk feeding initiation was examined in two different populations from the same study^40,38^ and therefore, there was not enough evidence to assess and draw a summary statement for human milk feeding initiation.

Insurance and any and exclusive human milk feeding duration, assessed categorically between 6 weeks to 6 months, was examined in two studies,^44,45^ and therefore, there was not enough evidence to assess and draw a summary statement for human milk feeding duration.

##### NIMHD framework: interpersonal level – biological domain

Within the interpersonal level and biological domain, the following factors were identified: birth weight,^5,40,45,50^ child sex,^51^ and infant health.^36^ There was not enough evidence to assess and draw a summary statement for child sex^51^ and poor infant health at birth.^36^

###### Birth weight

Birth weight was examined in four PCS,^5,40,45,50^ two of which examined human milk feeding initiation,^5,40^ and three of which examined human milk feeding duration,^5,45,50^ assessed categorically between 6 weeks to 6 months or longer. One study also examined meeting intention to breastfeed for 6 months as an outcome, which is described with human milk feeding duration.^45^

Birth weight and human milk feeding initiation was examined in two studies^5,40^; therefore, there was not enough evidence to assess and draw a summary statement for birth weight and human milk feeding initiation.

Birth weight and any and exclusive human milk feeding duration, assessed categorically between 6 weeks to 6 months, was examined in three studies,^5,45,50^ two of which examined mediation^45,50^ and one of which examined moderation by stratifying by race and ethnicity.^5^ All three studies examined Black and White mothers,^5,45,50^ and one study examined Hispanic mothers.^5^ Both mediation studies reported that infant weight (low birth weight more common among Black than White mothers) significantly mediated the association between race (Black versus White) and exclusive human milk feeding.^45,50^ However, results were mixed for any human milk feeding for Black and White mothers, with one study reporting null results for any breastfeeding at 6 months^45^ and the other study reporting that infant weight greater than or equal to 2500 grams (lower in U.S.-born Black mothers than U.S.-born White mothers) mediated the relationship between race and any breastfeeding at 2-6 months.^50^ In the study that stratified by race and ethnicity, a smaller proportion of Hispanic, White, and Black mothers breastfed for 6 months or longer if they had low birth weight infants compared to normal birth weight infants in one or more survey years of the study (other survey years were non-significant).^5^ In contrast, a smaller proportion of very low birth weight infants, compared to normal birth weight infants, were breastfed for at least 6 months among White mothers, but not for Hispanic or Black mothers.^5^ In general, results were mixed, varying by the type of outcome (any or exclusive human milk feeding duration).

Although there were not enough studies for birth weight and human milk feeding initiation, the evidence for birth weight and human milk feeding duration was assessed using the following domains:

- [underlined: Consistency]: For birth weight, results were inconsistent in significance for human milk feeding duration. Among the significant findings, the evidence had consistent directionality, with shorter human milk feeding duration in Black mothers compared to White mothers was mediated by higher rates of low birth weight in Black mothers.
- [underlined: Precision]: Study effect estimates and confidence intervals were not examined. Sample sizes ranged from n=205 to 44,155 for birth weight.
- [underlined: Risk of bias]: There is a concern for risk of bias due to confounding for all observational studies. However, risk of bias due to confounding was not formally examined for this rapid review question because a discrete list of key confounders could not be identified a priori due to the exploratory nature of the rapid review. Risk of bias was low or moderate for selection of participants into the study, classification of exposures, deviations from intended exposures, and measurement of the outcome. Two studies did not have information regarding missing data. One study had serious risk of bias for selection of reported results due to inconsistent reporting of significant and non-significant results.
- [underlined: Directness]: All studies aligned with the population, exposure, comparator, and outcomes in the analytic framework.
- [underlined: Generalizability]: The evidence for birth weight is generalizable to the United States.

Summary statement: There is not enough consistent evidence among the small number of studies to determine whether birth weight is associated with racial and ethnic disparities in human milk feeding duration.

##### NIMHD framework: interpersonal level – behavioral domain

Within the interpersonal level and behavioral domain, the following factors were identified: employment^22,34,40,43,50,65,66^ and violence exposure.^23,40^ There were too few studies on violence exposure, which included sexual abuse as child or physical abuse when younger, history of violence exposure,^23^ current partner arguments, and living in unsafe neighborhoods,^23^ and suffering abuse during pregnancy by others,^40^ to assess the evidence and draw a summary statement.

###### Employment

Employment, including aspects of employment were examined in seven articles^22,34,40,43,50,65,66^ (five PCS,^34,43,50,65,66^ two cross-sectional)^22,40^ from five cohorts; four articles from three cohorts examined human milk feeding initiation^34,40,65,66^ while five articles from three cohorts examined any and exclusive human milk feeding duration,^22,43,50,65,66^ assessed continuously and categorically between 2 to 6 months.

Employment and human milk feeding initiation was examined in four articles^34,40,65,66^ (three cohorts), one of which tested mediation,^65^ two of which tested moderation by interaction,^34,66^ and one of which stratified by race.^40^ The various aspects of employment included planning to work outside the home,^34^ currently working or going to school,^40^ salaried prior to delivery,^40^ occupation,^66^ job control,^65^ and physical workload.^65^ The one mediation analysis examined physical workload and job control between Black versus White and other versus White mothers,^65^ the two moderation analyses examined occupation^66^ and planning to work outside home^34^ between Black, White, and other mothers,^34,66^ and the stratified analyses examined currently working or going to school or salaried prior to delivery among Black and White mothers.^40^ All analyses except for those on job control reported null results. For job control, low job control (higher in Black mothers) mediated the relationship between race (Black versus White mothers) and initiation (lower in Black mothers), but not when comparing Other mothers to White mothers.^65^ Taken together, aspects of employment did not generally mediate or moderate the association between race and human milk feeding initiation among Black, Other, and White women.

Employment and any or exclusive human milk feeding duration, assessed continuously and categorically between 2 to 6 months, was examined in five studies,^22,43,50,65,66^ three of which tested mediation,^43,50,65^ two of which tested moderation by interaction,^22,66^ and one of which stratified by race.^66^ Aspects of employment included working,^43^ employment outside the home prior to giving birth,^50^ job control^65^ and physical workload.^65^ The three studies that tested mediation reported a mix of null^43,50,65^ and significant findings^50,65^ due to multiple analyses. All three studies compared between Black and White mothers, one study compared between Other versus White mothers,^65^ and one study compared Spanish- or English-speaking Hispanic to White or to Black mothers.^43^ When comparing Black to White mothers, working^43^ and physical workload^65^ did not mediate the relationship between race and mean breastfeeding duration and breastfeeding for 6 months, respectively, while low job control significantly mediated the association between race and breastfeeding at 6 months.^65^ Additionally, there were mixed findings for employment outside the home; this factor did not mediate the relationship between race and any breastfeeding at 2 to 6 months, but significantly mediated the relationship between race and exclusive breastfeeding at 2 to 6 months.^50^ One study compared between foreign-born Black mothers to U.S.-born White mothers and reported that employment outside the home did not mediate the relationship between race and either any or exclusive breastfeeding at 2 to 6 months.^50^ The one study that compared Hispanic to White or Black mothers found that working did not mediate the relationship between race and ethnicity and mean breastfeeding duration.^43^ The one study comparing Other to White mothers reported that neither job control and nor physical workload mediated the relationship between race and ethnicity and breastfeeding at 6 months.^65^ Among the two moderation by interaction studies,^22,66^ one study reported a null interaction between race and ethnicity (White, Native Hawaiian, Samoan, Filipino, Japanese, Chinese, Korean, Black, Other/unknown) and return to work/school,^22^ while the second study reported a significant interaction between race (Black, Other versus White) and type of employment, which was further stratified by race.^66^ When stratified by race, breastfeeding duration was longest among Black mothers with professional/managerial occupations and shorter for Black mothers who do not work and who work in service/labor occupation, while among White mothers, breastfeeding duration was longest for mothers not working, followed by professional/managerial work, and shortest duration was observed for service/labor workers.^66^ In summary, there were mixed findings for the mediation and moderation analyses that varied by outcome (any or exclusive breastfeeding), racial and ethnic comparisons, and by the aspect of employment variable.

The evidence was assessed using the following domains:

- [underlined: Consistency]: The aspects of employment assessed across studies varied, which included returning to work/school, job control, physical workload, and occupation type, although the most commonly examined employment factor was whether the woman was working or would be working. When examining all employment-related factors together, studies were less consistent for any and exclusive human milk feeding duration, relative to human milk feeding initiation; results varied by the aspect of employment variable, outcome, and racial and ethnic comparisons.
- [underlined: Precision]: Study effect estimates and confidence intervals were not examined. Sample sizes were relatively small, ranging from n=450 to n=2,036 in these six studies.
- [underlined: Risk of bias]: There is a concern for risk of bias due to confounding for all observational studies. However, risk of bias due to confounding was not formally examined for this rapid review question because a discrete list of key confounders could not be identified a priori due to the exploratory nature of the rapid review. The majority of studies had low risk of bias for selection of participants into the study, classification of exposures, and deviations from intended exposures. The majority of studies had moderate risk of bias for measurement of the outcome and selection of reported results. One study had serious risk of bias for selection of reported results due to selective and inconsistent reporting of significant and non-significant results. Four of seven studies had moderate risk of bias for missing data, while two had low risk of bias, and one had no information.
- [underlined: Directness]: All studies aligned with the population, exposure, comparator, and outcomes in the analytic framework.
- [underlined: Generalizability]: The evidence is generalizable to the United States population.

Summary statement: Evidence suggests that employment or aspects of employment may not be associated with disparities in human milk feeding initiation between Black, Other, and White mothers. There is not enough consistent evidence among the heterogeneous variables related to employment to determine whether employment is associated with disparities in human milk feeding duration between Black and White mothers.

##### NIMHD framework: interpersonal level – physical/built environment domain

Within the interpersonal level and physical/built environment, the following factor was identified: household environment-related variables,^36,40^ which included insufficient privacy/space in home,^36^ unstable housing before birth,^36^ number of people living with mother,^40^ recent move prior to pregnancy,^40^ and rooms in the residence.^40^ However, there were too few studies to assess the evidence and draw a summary statement for household environment-related variables.

##### NIMHD framework: interpersonal level – sociocultural environment domain

Within the interpersonal level and sociocultural environment domain, the following factors were identified: coresident father,^11,43^ coresident grandparent,^43^ paternal education,^36^ paternity acknowledgement,^59^ paternal race and ethnicity,^9,49,60^ paternal nativity,^9^ marital status,^13,28,30,34,36,40,43,45,60,61,67^ maternal or paternal grandmother breastfed their own child,^43^ social support,^6,14,64^ mother/partner as primary caretakers,^50^ and subjective norms.^50^ There was not enough evidence to draw summary statements for the following factors: coresident father,^11,43^ coresident grandparent,^43^ paternity acknowledgement,^59^ paternal education,^36^ paternal nativity,^9^ maternal or paternal grandmother breastfed their own child,^43^ mother/partner as primary caretakers,^50^ and subjective norms.^50^

###### Marital status

Marital status was examined in 11 articles^13,28,30,34,36,40,43,45,60,61,67^ (4 PCS,^34,36,43,45^ 7 cross-sectional),^13,28,30,40,60,61,67^ 9 (from 10 articles) of which examined human milk feeding initiation,^13,28,30,34,36,40,43,60,61,67^ and three of which examined any or exclusive human milk feeding duration,^36,43,45^ assessed continuously and categorically between 6 weeks to 8 months. One study also examined meeting intention to breastfeed for 6 months as an outcome, which is described with human milk feeding duration.^45^

Marital status and human milk feeding initiation, including breastfeeding for at least 1 week, was examined in 10 studies,^13,28,30,34,36,40,43,60,61,67^ one of which tested mediation,^43^ five of which examined moderation by interaction or effect modification,^13,30,34,36,60^ two of which stratified only by race and ethnicity,^28,40^ one of which stratified only by marital status,^61^ and one of which stratified by race and ethnicity and by multiple factors.^67^ The one study on mediation reported mixed findings: marital status was a significant mediator of the relationship between race and ethnicity and breastfeeding initiation for Black versus White mothers, but not for Hispanic versus White or Black mothers.^43^ Four of the five studies that examined interactions or effect modification reported null interactions between marital status and race and ethnicity between Black, Hispanic, Other, and White mothers.^13,30,34,36^ One of these studies compared married/cohabiting to not married/cohabiting, little chance of marriage.^36^ One study reported that marital status was a significant effect modifier of the association between race and ethnicity and breastfeeding initiation between Black, White, and Hispanic mothers, but directionality was not reported.^61^ Findings were mixed for the two studies that stratified by race and ethnicity.^28,40^ One study reported significantly higher odds of breastfeeding initiation with marriage among Black mothers while marital status was not retained in the model among White mothers^40^; the second study found significant associations in the same direction between marital status and breastfeeding initiation among all racial and ethnic groups (Black, Hispanic, Other, White mothers).^28^ The study that stratified by marital status reported that married and unmarried Hispanic and other non-Hispanic mothers had lower breastfeeding non-initiation compared to non-Hispanic White mothers, while differences between non-Hispanic Black and non-Hispanic White mothers were null among both married and unmarried women.^61^ Finally, one study examined the impact of income on human milk feeding initiation stratified by marital status, preterm birth, and race and ethnicity, and was difficult to interpret.^67^ Taken together, this evidence suggests that marital status may not mediate or moderate the association between race (Black, Hispanic, Other, and White mothers) and human milk feeding initiation.

Marital status and any and exclusive human milk feeding duration, assessed continuously and categorically between 6 weeks to 8 months, was examined in three studies,^36,43,45^, two of which tested mediation^43,45^ and one of which tested moderation by interaction.^36^ The two mediation studies reported inconsistent results.^43,45^ One study reported that being married or part of a couple, compared to single/divorced/separated, did not significantly mediate the relationship between race (Black versus White mothers) on exclusive breastfeeding at 6 weeks, any breastfeeding at 6 months, or meeting 6 month intention to breastfeed.^45^ The second study reported both significant and null findings, finding that marriage (lower in Black mothers; higher in English-speaking Hispanic mothers), compared to single or in a relationship, significantly mediated the relationship between race (Black versus White mothers; English-speaking Hispanic versus Black mothers) and mean breastfeeding duration (lower in Black mothers; higher in English-speaking Hispanic mothers); however, this was not significant when comparing Spanish-speaking Hispanic mothers to Black mothers.^43^ The one study that tested an interaction reported that marital status did not interact significantly with race and ethnicity (Black, Hispanic versus White mothers) to impact breastfeeding duration up to 8 months.^36^ Taken together, it is unclear whether marital status mediates or moderates the relationship between race and ethnicity and any or exclusive human milk feeding duration.

The evidence was assessed using the following domains:

- [underlined: Consistency]: Evidence for marital status was relatively consistent when examining studies that tested mediation or moderation by interaction for human milk feeding initiation, with studies primarily suggesting that marital status did not mediate or moderate associations between race and ethnicity and human milk feeding initiation among Black, Other, and White mothers. Evidence for human milk feeding duration was not consistent in significance.
- [underlined: Precision]: Study effect estimates and confidence intervals were not examined. Sample sizes varied from n=450 to n=840,887 for marital status. However, most studies had sample sizes less than n=8,000.
- [underlined: Risk of bias]: There is a concern for risk of bias due to confounding for all observational studies. However, risk of bias due to confounding was not formally examined for this rapid review question because a discrete list of key confounders could not be identified a priori due to the exploratory nature of the rapid review. All studies had low risk of bias for selection of participants into the study, classification of exposures, and deviations from intended exposures. The majority of studies had moderate risk of bias for measurement of the outcome, with low risk of bias for the remaining studies. The majority of studies had moderate risk of bias for selection of reported results, although one study had a serious risk of bias due to selective reporting of significant findings. Finally, approximately half of studies had moderate risk of bias for missing data, with the remaining studies assessed as either low, serious, or no information.
- [underlined: Directness]: All studies aligned with the population, exposure, comparator, and outcomes in the analytic framework.
- [underlined: Generalizability]: The evidence is generalizable to the United States population.

Summary statement: Evidence suggests that marital status may not be associated with racial and ethnic disparities in human milk feeding initiation. There is not enough consistent evidence among the small number of studies to determine whether marital status is associated with racial and ethnic disparities in human milk feeding duration.

###### Paternal race and ethnicity

Paternal race and ethnicity was examined in three studies,^9,49,60^ (one PCS,^49^ two cross-sectional),^9,60^ all of which examined human milk feeding initiation,^9,49,60^ and one of which examined exclusive breastfeeding at 30 days.^49^

Paternal race and ethnicity and human milk feeding initiation, including exclusive breastfeeding at discharge, was examined in three studies,^9,49,60^ two of which incorporated paternal race and ethnicity into a single variable with maternal race and ethnicity,^49,60^ and one of which stratified by maternal race and ethnicity.^9^ All studies reported significant associations,^9,49,60^ and one study reported null associations due to multiple analyses.^49^ One study reported significantly higher odds of exclusive breastfeeding at discharge when neither parent was Hispanic compared to when both parents were Hispanic,^49^ while results were null when comparing when only one parent (father or mother in separate analyses) was Hispanic to when both parents were Hispanic.^49^ In another study, having a Black father and White mother and having a White father and Black mother were associated with significantly lower odds of initiation compared to White father and White mothers.^60^ In the same study, having a Hispanic father and White mother, having a Hispanic father and Black mother, having a Black father and Hispanic mother, and having a White father and Hispanic mother were associated with significantly higher initiation than having a White father and White mother.^60^ The study that stratified by maternal race and ethnicity reported significantly higher initiation with U.S.-born Other ethnicity fathers to U.S.-born White fathers among both U.S.-born White mothers and U.S.-born other ethnicity mothers.^9^ Taken together, while differences in human milk feeding initiation by maternal race and ethnicity may vary by paternal race and ethnicity, there are not enough studies for any particular comparison to evaluate trends consistently.

Paternal race and ethnicity and exclusive human milk feeding duration at 30 days was examined in one study^49^; therefore, there was not enough evidence to assess evidence draw a summary statement in human milk feeding duration.

Although there were not enough studies for paternal race and ethnicity and human milk feeding duration, the evidence for paternal race and ethnicity and human milk feeding initiation was assessed using the following domains:

- [underlined: Consistency]: Studies on paternal race and ethnicity generally reported significant results, with all three studies reporting moderation by this variable. However, there weren’t enough studies on a single race and ethnicity to assess consistency within racial and ethnic groups.
- [underlined: Precision]: Study effect estimates and confidence intervals were not examined. Sample sizes ranged from n=499 to n=1,053,096.
- [underlined: Risk of bias]: There is a concern for risk of bias due to confounding for all observational studies. However, risk of bias due to confounding was not formally examined for this rapid review question because a discrete list of key confounders could not be identified a priori due to the exploratory nature of the rapid review. Risk of bias was low for selection of participants into the study, classification of exposures, and deviations from intended exposures. All studies had serious risk of bias for missing data and moderate risk of bias for selection of reported results, while the majority had low risk of bias for measurement of outcomes.
- [underlined: Directness]: All studies aligned with the population, exposure, comparator, and outcomes in the analytic framework.
- [underlined: Generalizability]: The evidence is generalizable to the United States population.

Summary statement: There is not enough consistent evidence among the small number of studies to determine whether paternal race and ethnicity is associated with racial and ethnic disparities in human milk feeding initiation.

###### Social support

Social support was examined in three articles^6,14,64^ (two cross-sectional,^6,64^ one RCS),^14^ one of which examined human milk feeding initiation,^14^ and all of which examined any or exclusive human milk feeding duration,^6,14,64^ assessed categorically between 2 to 10 weeks.

Social support and human milk feeding initiation was examined in one study,^14^ and therefore, evidence was not synthesized and a summary statement was not drawn.

Social support and any or exclusive human milk feeding duration was examined in three studies, all of which examined moderation.^6,14,64^ Two studies examined moderation by interaction,^14,64^ one of which was further stratified by race and ethnicity,^64^ and one study stratified by social support.^6^ The factors related to social support varied, including social network (exclusive network versus expansive network),^6^ breastfeeding discouragement,^14^ and emotional or financial support.^64^ Three of the four analyses of social support variables were null, including breastfeeding discouragement among Hispanic, Black, and White mothers,^14^ and instrumental (financial) or emotional support among Hispanic, Black, non-Hispanic Other, and White mothers.^64^ The one study that stratified by social support reported that Black race, compared to White race, was positively associated with exclusive breastfeeding and mixed feeding for mothers with an exclusive network with primarily kin centric individuals 15 years or older but not for mothers with expansive networks.^6^ Overall, studies reported mixed findings within the few studies that examined social support and human milk feeding duration.

Although there were not enough studies for social support and human milk feeding initiation, the evidence for social support and human milk feeding duration was assessed using the following domains:

- [underlined: Consistency]: Studies on social support varied in significance, with two of three studies reporting null results.
- [underlined: Precision]: Study effect estimates and confidence intervals were not examined. Sample sizes ranged from n=402 to n=5,378.
- [underlined: Risk of Bias]: There is a concern for risk of bias due to confounding for all observational studies. However, risk of bias due to confounding was not formally examined for this rapid review question because a discrete list of key confounders could not be identified a priori due to the exploratory nature of the rapid review. Risk of bias was low for selection of participants into the study and deviations from intended exposures, and moderate for risk of bias due to measurement of the outcome and selection of reported results. The majority of studies were assessed as having low risk of bias for classification of exposures and missing data.
- [underlined: Directness]: All studies aligned with the population, exposure, comparator, and outcomes in the analytic framework.
- [underlined: Generalizability]: The evidence is generalizable to the United States population.

Summary statement: There is not enough consistent evidence among the small number of studies to determine whether social support is associated with racial and ethnic disparities in human milk feeding duration.

##### NIMHD framework: community level – biological domain

Within the community level and biological domain, the following factor was identified: coronavirus pandemic.^17^ However, there was not enough evidence to assess and draw a summary statement for this factor.

##### NIMHD framework: community level – physical/built environment domain

Within the community level and physical/built environment, the following factors were identified: geographic location (residing in the United States-Mexico border versus non-residing),^58^ military affiliation,^38^ neighborhood characteristics,^35,69^ urbanicity,^20,26,39,40,53^ and WIC participation.^13,15,18,28,36,41,43,50,53,54,71^ The following factors did not have enough evidence to assess and draw a summary statement: geographic location,^58^ military affiliation,^38^ and neighborhood characteristics (i.e., neighborhood physical amenities, supportive neighborhood, neighborhood safety, neighborhood disadvantage, and neighborhood affluence).^35,69^

###### Urbanicity

Urbanicity was examined in five studies^20,26,39,40,53^ (three PCS,^20,39,53^ two cross-sectional)^26,40^ from three cohorts, all of which examined human milk feeding initiation, and one of which examined human milk feeding duration at 8 weeks or longer.^20^

Urbanicity and human milk feeding initiation was examined in five articles (three cohorts), all of which tested moderation.^20,26,39,40,53^ One article tested moderation by interaction,^53^ two studies stratified by urbanicity,^26,39^ one study stratified by race,^40^ one study stratified by race and ethnicity and urbanicity,^39^ and one study had unclear methods.^20^ Four studies examined Black and White mothers,^20,26,39,40^ four studies examined Hispanic mothers,^20,26,39,53^ and two studies examined Asian or American Indian mothers.^26,53^ Findings of studies were mixed. When examining Black and White mothers, three of four articles suggested that urbanicity did not moderate the relationship between race and initiation,^20,26,39^ while two studies suggested significant moderation by urbanicity.^39,40^ Of these, one reported higher and lower odds of initiation in mixed rural and mixed urban locations, respectively, among White mothers compared to Black mothers^39^; the last study reported that Black mothers with less than 12 years of education had significantly higher initiation with urban residence, which was not retained in the model for White mothers.^40^ One study reported a significant interaction between rural residence (versus urban) and race and ethnicity, such that foreign-born Mexican-origin Hispanic mothers had higher odds of initiation, Black mothers had lower initiation, and mothers of other racial and ethnic groups (U.S.-born Mexican origin Hispanic, Native American, Asian, Other Hispanics) had no significant differences when compared to non-Hispanic White mothers.^53^ Two studies compared Hispanic mothers to White mothers,^20,26^ one of which had significant results but the interpretation of results was unclear.^20^ The remaining study reported significantly higher initiation among Hispanic mothers in both urban and rural areas.^26^ The studies that examined Black and White mothers or Hispanic and White mothers were mixed in significance and in directionality. Additionally, there were not enough studies for any single comparison between mothers of different racial and ethnic groups to draw summary statements.

Urbanicity and human milk feeding duration, assessed at 8 weeks or longer, was examined in one study^20^ and therefore, evidence was not synthesized and a summary statement was not drawn.

Although there were not enough studies for urbanicity and human milk feeding duration, the evidence for urbanicity and human milk feeding initiation was assessed using the following domains:

- [underlined: Consistency]: Studies varied in significance and directionality within racial and ethnic comparisons.
- [underlined: Precision]: Effect estimates and confidence intervals were not examined. Sample sizes ranged from n=2,036 to n=240,054.
- [underlined: Risk of bias]: There is a concern for risk of bias due to confounding for all observational studies. However, risk of bias due to confounding was not formally examined for this rapid review question because a discrete list of key confounders could not be identified a priori due to the exploratory nature of the rapid review. All studies that examined urbanicity had low risk of bias for selection of participants into the study, classification of exposure, and deviations from intended exposures. Two studies had moderate risk of bias for missing data, while two studies did not provide enough information on missing data. One study had serious risk of bias for selection of reported results due to inconsistent reporting of results depending on the outcome.
- [underlined: Directness]: Studies that examined urbanicity were less direct due to stratification by race and ethnicity and by urbanicity in majority of studies. Most studies for human milk feeding initiation conducted analyses of urbanicity stratified by race and ethnicity or stratified by urbanicity, which may be less direct than assessing moderation by testing interactions.
- [underlined: Generalizability]: The evidence is generalizable to the United States.

Summary statement: There is not enough consistent evidence among the small number of studies to determine whether urbanicity is associated with racial and ethnic disparities in human milk feeding initiation.

###### WIC participation

WIC participation was examined in 11 articles^13,15,18,28,36,41,43,50,53,54,71^ (7 PCS,^15,18,36,43,50,53,54^ 4 cross-sectional)^13,28,41,71^ from 10 cohorts, 7 of which examined human milk feeding initiation^13,18,28,41,43,53,71^ and 6 of which examined any or exclusive human milk feeding duration,^15,36,41,43,50,54^ assessed continuously and categorically between 1 and 12 months.

WIC participation and human milk feeding initiation was examined in seven studies,^13,18,28,41,43,53,71^ one of which tested mediation,^43^ three of which examined moderation by interaction,^13,18,53^ and four of which stratified by race and ethnicity.^18,28,41,71^ The one study that tested mediation reported that WIC participation did not mediate the relationship between race and ethnicity and initiation between Black, Hispanic, and White mothers.^43^ Among the three studies that tested interactions,^13,18,53^ both studies that examined Hispanic ethnicity reported higher human milk feeding initiation with WIC participation for Hispanic mothers relative to non-Hispanic mothers,^13,53^ while comparisons between Black, White, and Other mothers were mixed^13,18,53^: one study reported significantly lower non-initiation with WIC participation for Black mothers compared to White mothers but no differences when comparing Other mothers to White mothers,^13^ one study reported a significant interaction, with higher initiation with prenatal WIC participation among White, but not Black mothers,^18^ and one study found no difference when comparing Black and White mothers.^53^ Among the four studies that stratified by race and ethnicity,^18,28,41,71^ three studies reported significant associations between WIC participation and initiation among White mothers, but no association among Black mothers.^18,28,41^ However, the directionalities of the significant findings among White mothers were mixed, with two studies reporting lower odds of initiation for WIC participation during pregnancy,^28,41^ and one study reporting higher initiation with prenatal WIC participation for 3 months or longer.^18^ One study reported null findings among White, Black, Hispanic, and Other mothers.^71^ Taken together, findings suggest that WIC participation may impact human milk feeding initiation differently among Black and White mothers, however, direction of associations were inconsistent for Black, White, and Hispanic mothers.

WIC participation, prenatally or postnatally, and any and exclusive human milk feeding duration, assessed continuously and categorically between 1 and 12 months, was examined in six studies.^15,36,41,43,50,54^ Two tested mediation,^43,50^ three tested moderation by interaction,^15,36,54^ and one stratified by race.^41^ The two studies on mediation reported mixed findings,^43,50^ with one study finding that WIC participation did not mediate the relationship between race and ethnicity and breastfeeding duration between Black, Hispanic, and White mothers,^43^ and one study finding that WIC participation significantly mediated the association between race and any and exclusive breastfeeding at 2 to 6 months between Black and White mothers.^50^ Two of the three studies that tested moderation by interaction reported null interactions between prenatal or postpartum WIC participation and race and ethnicity between Black, Hispanic, White and Other mothers.^15,36^ The third study detected a significant interaction, such that other Hispanic mothers were more likely to continue breastfeeding than non-Hispanic White mothers among WIC participants; differences in duration did not vary between non-Hispanic White mothers and mothers of other races/ethnicities, including Foreign-born Mexican-origin Hispanic, U.S.-born Mexican-origin Hispanic, Non-Hispanic Black, Native American, and Asian mothers who participated in WIC.^54^ The one study that stratified by race reported null associations between prenatal WIC participation and breastfeeding duration at 10 weeks among both Black and White mothers.^41^ Taken together, studies suggest that WIC participation may not moderate the association between race and ethnicity (Black, Hispanic, and White mothers) and human milk feeding duration.

The evidence was assessed using the following domains:

- [underlined: Consistency]: Studies on WIC participation and human milk feeding initiation were inconsistent in significance and directionality for Black and White mothers. Studies on initiation for Hispanic mothers had mixed results. Studies on WIC participation and human milk feeding duration were somewhat consistent with more null associations than significant findings.
- [underlined: Precision]: Study effect estimates and confidence intervals were not examined. The majority of studies examining WIC participation had sample sizes from n=1,000 to 11,000, although one study had a sample size of n=501,967.
- [underlined: Risk of bias]: There is a concern for risk of bias due to confounding for all observational studies. However, risk of bias due to confounding was not formally examined for this rapid review question because a discrete list of key confounders could not be identified a priori due to the exploratory nature of the rapid review. The majority of studies had low risk of bias for selection of participants into the study, classification of exposures, and deviations from intended exposures. The majority of studies had moderate risk of bias for measurement of the outcome and selection of reported results. Approximately a third of studies had low and a third had moderate risk of bias for missing data, while few had no information and few had serious risk of bias for this domain due to high rates of missing data.
- [underlined: Directness]: All studies aligned with the population, exposure, comparator, and outcomes in the analytic framework. Approximately half of studies conducted analyses of WIC participation stratified by race and ethnicity, which may be less direct than assessing moderation by testing interactions.
- [underlined: Generalizability]: The evidence is generalizable to populations with low-income in the United States.

Summary statement: Evidence suggests that prenatal or postpartum WIC participation may not be associated with the relationship between race and ethnicity and human milk feeding duration among Black, Hispanic, and White mothers. There is not enough consistent evidence to determine whether WIC participation is associated with racial and ethnic disparities in human milk feeding initiation.

##### NIMHD framework: community level – health care system domain

Within the community level and health care system domain, the following factors were identified: baby-friendly hospital practices,^2,3,40,43,45^ NICU,^13,16,28^ breastfeeding information from hospital staff,^36,40^ type of birth attendant,^19^ prenatal care,^28,40^ hospital level of perinatal care,^46^ labor anesthesia,^13^ and medical conditions or labor/delivery complications.^32^ The following factors did not have enough evidence to assess the evidence and draw a summary statement: breastfeeding information from hospital staff,^36,40^ type of birth attendant,^19^ prenatal care,^28,40^ hospital level of perinatal care,^46^ labor anesthesia,^13^ and medical conditions or labor/delivery complications.^32^

###### Baby-friendly hospital practices

Baby-friendly hospital practices were examined in five studies^2,3,40,43,45^ (three PCS,^3,43,45^ two cross-sectional),^2,40^ four of which examined human milk feeding initiation^2,3,40,43^ and three of which examined any or exclusive human milk feeding duration,^2,43,45^ assessed continuously and categorically between 6 weeks to 6 months. One study also examined meeting intention to breastfeed for 6 months as an outcome, which is described with human milk feeding duration.^45^

Baby-friendly hospital practices and human milk feeding initiation, including exclusive breastfeeding during maternity hospitalization,^3^ was examined in four studies.^2,3,40,43^ Factors related to baby-friendly hospital practices varied and included state-level baby-friendly hospital practices,^2^ skin-to-skin contact,^3^ breastfeeding in the first hour,^40^ breastfeeding in the hospital,^40^ and in-hospital formula.^43^ One study examined mediation on in-hospital formula use,^43^ two studies examined moderation by interaction (one on skin-to-skin contact^3^ and one on state-level baby-friendly hospital practices),^2^ and two studies stratified by race and ethnicity (one on state-level baby-friendly hospital practices^2^ and one on breastfeeding in the first hour and breastfeeding in the hospital).^40^ The mediation analysis on in-hospital formula between Black, Hispanic, and White mothers,^43^ the moderation by interaction for skin-to-skin contact between African American, Caucasian, Hispanic, and other mothers,^3^ and state-level baby-friendly hospital practices between Hispanic, non-Hispanic Black, and White mothers^2^ all reported null results. When examining the stratified analyses, three of the four factors reported null associations between the factor related to baby-friendly hospital practices and human milk initiation for all racial and ethnic groups examined: mPINC scores among Black, White, and Hispanic mothers,^2^ breastfeeding in the first hour among Black and White mothers,^40^ and breastfeeding in the hospital among Black and White mothers (not retained in the model).^40^ One study reported significant associations between breastfeeding in the hospital and human milk feeding initiation among both Black and White mothers.^40^ Although the baby-friendly hospital factors examined different aspects of the baby-friendly hospital initiative, studies suggest that these practices do not mediate or moderate the association between race and ethnicity (Black, Hispanic, and White mothers) and human milk feeding initiation.

Baby-friendly hospital practices and any and exclusive human milk feeding duration, assessed continuously and categorically between 6 weeks and 6 months, was examined in three studies,^2,43,45^ two of which examined mediation (one on in-hospital formula^43^ and one on baby-friendly hospital status)^45^ and one study on state-level baby-friendly hospital practices which examined moderation by interaction and stratified by race and ethnicity.^2^ All three studies reported both significant and null findings, with no clear pattern of results. One of the two mediation studies reported that in-hospital formula significantly mediated the relationship between race and breastfeeding duration when comparing Black to White mothers, but this was null when comparing Hispanic to White or Black mothers.^43^ The second mediation study reported that baby-friendly hospital status significantly mediated the relationship between race for exclusive breastfeeding at 6 weeks between Black and White mothers, but this was null for breastfeeding at 6 months and meeting breastfeeding intention for 6 months.^45^ The third study reported null interaction between baby-friendly hospital practices and race and ethnicity (non-Hispanic White, non-Hispanic Black, Hispanic) on duration to at least 6 months; however, when stratified by race and ethnicity (non-Hispanic White, non-Hispanic Black, Hispanic), mothers who received more maternity care practices compared to less maternity care practices had higher odds of breastfeeding to 6 months among non-Hispanic White mothers, but not for non-Hispanic Black or Hispanic mothers.^2^ Taken together, the few studies had mixed findings.

The evidence was assessed using the following domains:

- [underlined: Consistency]: Studies were consistent for human milk feeding initiation, with all studies suggesting that baby-friendly hospital practices did not mediate or moderate the relationship between race and ethnicity and human milk feeding initiation. Studies for human milk feeding duration were inconsistent in significance, without a clear pattern of results within racial and ethnic comparisons.
- [underlined: Precision]: Study effect estimates and confidence intervals were not examined for these studies. Sample sizes ranged from n=205 to 25,036.
- [underlined: Risk of bias]: There is a concern for risk of bias due to confounding for all observational studies. However, risk of bias due to confounding was not formally examined for this rapid review question because a discrete list of key confounders could not be identified a priori due to the exploratory nature of the rapid review. The majority of studies had low risk of bias for selection of participants into the study and classification of exposures. One study had serious risk of bias for selection of participants into the study due to follow-up and exposure not coinciding for most participants and one study had moderate risk of bias for classification of exposures. All studies had low risk of bias for deviations from intended exposures. Approximately half of studies had moderate and half had low risk of bias for missing data. The majority of studies had moderate risk of bias for measurement of outcomes and selection of reported results. One study had low risk of bias for measurement of the outcome and one study had serious risk of bias for selection of reported results due to inconsistent reporting of results depending on the outcome.
- [underlined: Directness]: All studies aligned with the population, exposure, comparator, and outcomes in the analytic framework.
- [underlined: Generalizability]: The evidence is generalizable to the United States population.

Summary statement: Evidence suggests that baby-friendly hospital practices may not be associated with the relationship between race and ethnicity and human milk feeding initiation for Black, Hispanic, and White mothers. There is not enough consistent evidence among the small number of studies to determine whether baby-friendly hospital practices are associated with racial and ethnic disparities in human milk feeding duration.

###### NICU

NICU was examined in three studies,^13,16,28^ all of which were cross-sectional and examined human milk feeding initiation. One study examined moderation by interaction,^13^ one study stratified by race and ethnicity,^28^ and one study stratified by NICU admission.^16^ The study that tested interactions between race and ethnicity and NICU admission did not detect moderation between Hispanic, Black, Other, and White mothers.^13^ The other two studies suggested significant moderation.^16,28^ The first study, which stratified by race and ethnicity, reported lower odds of initiation with NICU admission among Hispanic and Non-Hispanic White mothers, but not for Non-Hispanic Black or Other mothers.^28^ The second study, which stratified by NICU admission, reported that Black mothers were more likely to not initiate breastfeeding compared to mothers of other races/ethnicities among infants who were not admitted to the NICU, while significant differences were not reported among infants who were admitted to the NICU.^16^ Taken together, studies reported mixed findings.

Although there were not enough studies for NICU and human milk feeding duration, the evidence for NICU and human milk feeding initiation was assessed using the following domains:

- [underlined: Consistency]: The findings of the studies were inconsistent in significance for human milk feeding initiation. Among the significant findings, one study stratified by NICU admission and one stratified by race, which made it difficult to compare across studies.
- [underlined: Precision]: Study effect estimates and confidence intervals were not examined for these studies. Sample sizes ranged from n=7,012 to n=1,317,535.
- [underlined: Risk of bias]: There is a concern for risk of bias due to confounding for all observational studies. However, risk of bias due to confounding was not formally examined for this rapid review question because a discrete list of key confounders could not be identified a priori due to the exploratory nature of the rapid review. All studies had low risk of bias for selection of participants into the study, classification of exposures, deviations from intended exposures, and measurement of the outcomes. All studies had moderate risk of bias for selection of reported results, and one study each was low, moderate, and serious for missing data.
- [underlined: Directness]: All studies aligned with the population, exposure, comparator, and outcomes in the analytic framework. Two-thirds of studies conducted analyses of NICU admission stratified by race and ethnicity or stratified by NICU admission, which may be less direct than assessing moderation by testing interactions.
- [underlined: Generalizability]: The evidence is generalizable to the United States population.

Summary statement: There is not enough consistent evidence among the small number of studies to determine whether NICU admission is associated with racial and ethnic disparities in human milk feeding initiation.

##### NIMHD framework: societal level – behavioral domain

Within the societal level and behavioral domain, the following factor was identified: maternity leave length.^33,47^ However, there is not enough evidence to determine whether maternity leave length is associated with racial and ethnic disparities in human milk feeding initiation and duration.^33,47^

Table 14 Risk of bias for observational studies that examined whether certain factors mediated or moderated the relationship between race and/or ethnicity and human milk feeding outcomes (Key Question 2)^*^

Article | Selection of participants | Classification of exposures | Deviations from intended exposures | Missing data | Outcome measurement | Selection of the reported results
Abuelezam, 2020^1^ | LOW | LOW | LOW | MODERATE | LOW | MODERATE
Belanoff, 2012^2^ | SERIOUS | LOW | LOW | MODERATE | MODERATE | MODERATE
Bramson, 2010^3^ | LOW | MODERATE | LOW | LOW | LOW | MODERATE
Buckman, 2020^4^ | LOW | LOW | LOW | MODERATE | MODERATE | MODERATE
Campbell, 2018^5^ | LOW | LOW | LOW | NO INFORMATION | MODERATE | MODERATE
Carlin, 2021^6^ | LOW | MODERATE | LOW | NO INFORMATION | MODERATE | MODERATE
Carswell, 2018^7^ | LOW | LOW | LOW | LOW | MODERATE | MODERATE
Chen, 2016^8^ | LOW | LOW | LOW | LOW | LOW | MODERATE
Cheng, 2018^9^ | LOW | LOW | LOW | SERIOUS | LOW | MODERATE
Chung, 2021^10^ | LOW | MODERATE | LOW | LOW | LOW | MODERATE
Corsack, 2022^11^ | LOW | LOW | LOW | LOW | MODERATE | MODERATE
Dabritz, 2010^12^ | LOW | LOW | LOW | LOW | MODERATE | MODERATE
Demirci, 2013^13^ | LOW | LOW | LOW | LOW | LOW | MODERATE
Fabiyi, 2021^14^ | LOW | LOW | LOW | LOW | MODERATE | MODERATE
Francescon, 2016^15^ | LOW | LOW | LOW | SERIOUS | MODERATE | MODERATE
Gertz, 2019^16^ | LOW | LOW | LOW | MODERATE | LOW | MODERATE
Glazer, 2022^17^ | LOW | LOW | LOW | LOW | LOW | MODERATE
Gyllstrom, 2021^18^ | LOW | LOW | LOW | LOW | LOW | MODERATE
Haile, 2017^19^ | LOW | LOW | LOW | SERIOUS | MODERATE | MODERATE
Hamilton, 2020^20^ | LOW | LOW | LOW | MODERATE | MODERATE | MODERATE
Hawkins, 2014^21^ | LOW | LOW | LOW | LOW | LOW | MODERATE
Hayes, 2014^22^ | LOW | MODERATE | LOW | MODERATE | MODERATE | MODERATE
Holland, 2018^23^ | LOW | LOW | LOW | SERIOUS | MODERATE | MODERATE
Holmes, 2011^24^ | LOW | MODERATE | LOW | MODERATE | MODERATE | MODERATE
Hughes, 2019^25^ | LOW | LOW | MODERATE | LOW | MODERATE | MODERATE
Jacobson, 2015^26^ | LOW | LOW | LOW | LOW | MODERATE | MODERATE
Jolles, 2022^27^ | LOW | LOW | LOW | NO INFORMATION | LOW | MODERATE
Kachoria, 2014^28^ | LOW | LOW | LOW | SERIOUS | LOW | MODERATE
Kachoria, 2014^29^ | LOW | SERIOUS | LOW | MODERATE | LOW | MODERATE
Kirksey, 2021^30^ | LOW | LOW | LOW | MODERATE | MODERATE | MODERATE
Kitsantas, 2011^31^ | LOW | SERIOUS | LOW | LOW | MODERATE | MODERATE
Kitsantas, 2010^32^ | LOW | LOW | LOW | NO INFORMATION | MODERATE | MODERATE
Kortsmit, 2021^33^ | LOW | LOW | LOW | MODERATE | MODERATE | MODERATE
Krause, 2011^34^ | LOW | LOW | LOW | LOW | MODERATE | MODERATE
Kummer, 2020^35^ | LOW | LOW | LOW | MODERATE | MODERATE | MODERATE
Lee, 2009^36^ | LOW | LOW | LOW | MODERATE | MODERATE | MODERATE
Liu, 2010^37^ | LOW | SERIOUS | LOW | LOW | MODERATE | MODERATE
Lundquist, 2015^38^ | LOW | LOW | LOW | NO INFORMATION | MODERATE | MODERATE
Lynch, 2012^39^ | LOW | LOW | LOW | MODERATE | LOW | MODERATE
Ma, 2012^40^ | LOW | LOW | LOW | NO INFORMATION | MODERATE | SERIOUS
Marshall, 2013^41^ | LOW | LOW | LOW | MODERATE | MODERATE | MODERATE
Masho, 2015^42^ | LOW | SERIOUS | LOW | MODERATE | MODERATE | MODERATE
McKinney, 2016^43^ | LOW | LOW | LOW | LOW | MODERATE | MODERATE
Mercier, 2018^44^ | LOW | LOW | LOW | MODERATE | LOW | MODERATE
Morrow, 2021^45^ | LOW | LOW | LOW | MODERATE | MODERATE | MODERATE
Nguyen, 2017^46^ | LOW | LOW | LOW | LOW | LOW | MODERATE
Ogbuanu, 2020^47^ | LOW | LOW | LOW | LOW | MODERATE | MODERATE
Orozco, 2021^48^ | LOW | LOW | LOW | LOW | MODERATE | MODERATE
Pithia, 2021^49^ | LOW | LOW | LOW | SERIOUS | MODERATE | MODERATE
Safon, 2021^50^ | LOW | MODERATE | LOW | MODERATE | MODERATE | MODERATE
Shafer, 2017^51^ | LOW | LOW | LOW | MODERATE | MODERATE | MODERATE
Sipsma, 2013^52^ | LOW | LOW | LOW | MODERATE | MODERATE | MODERATE
Sparks, 2011^54^ | LOW | LOW | LOW | LOW | MODERATE | MODERATE
Sparks, 2010^53^ | LOW | LOW | LOW | NO INFORMATION | MODERATE | MODERATE
Stevens, 2019^55^ | MODERATE | LOW | LOW | LOW | LOW | MODERATE
Tanda, 2018^56^ | LOW | LOW | LOW | MODERATE | MODERATE | MODERATE
Thompson, 2013^57^ | LOW | SERIOUS | LOW | LOW | LOW | MODERATE
Walker, 2014^58^ | MODERATE | LOW | LOW | LOW | LOW | MODERATE
Wallenborn, 2019^60^ | LOW | LOW | LOW | SERIOUS | LOW | MODERATE
Wallenborn, 2017^61^ | LOW | LOW | LOW | MODERATE | MODERATE | MODERATE
Wallenborn, 2017^62^ | LOW | LOW | LOW | SERIOUS | MODERATE | MODERATE
Wallenborn, 2018^59^ | LOW | LOW | LOW | MODERATE | LOW | MODERATE
Weiser, 2009^63^ | LOW | LOW | LOW | LOW | MODERATE | MODERATE
White, 2022^64^ | LOW | LOW | LOW | LOW | MODERATE | MODERATE
Whitley, 2021^66^ | LOW | LOW | LOW | MODERATE | MODERATE | MODERATE
Whitley, 2022^65^ | LOW | LOW | LOW | MODERATE | MODERATE | MODERATE
Wiener, 2016^67^ | LOW | LOW | LOW | MODERATE | MODERATE | MODERATE
Wouk, 2017^68^ | LOW | LOW | LOW | SERIOUS | MODERATE | MODERATE
Yourkavitch, 2018^69^ | LOW | LOW | LOW | LOW | LOW | MODERATE
Yu, 2013^70^ | LOW | LOW | LOW | NO INFORMATION | MODERATE | MODERATE
Zhang, 2021^71^ | LOW | LOW | LOW | NO INFORMATION | MODERATE | MODERATE

* Possible ratings of low, moderate, serious, critical, or no information determined using the “Risk of Bias for Nutrition Observational Studies” tool (RoB-NObs) ( Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC. )

### Qualitative studies

Seventy-two articles met the inclusion criteria for Key Question 2 that used a qualitative study design. The themes examined in these articles were organized using the NIMHD research framework (illustrated in Figure 9). Individual articles commonly addressed multiple themes. The characteristics and results of the included qualitative studies are presented in Appendix 7 (Table A-10).

Figure 9 Themes identified in qualitative articles included in Key Question 2 organized by the NIMHD research framework^a^ a Parentheses indicate the number of articles in which the themes were identified

This figure lists the themes identified in qualitative articles included in key question 2, organized by the NIMHD research framework. Individual level - biological domain: health issues (10 articles), physical breastfeeding problems (39 articles). Individual level - behavioral domain: breastfeeding beliefs, knowledge, and experiences (57 articles) which included breastfeeding attitudes (14 articles), breastfeeding being convenient or easy (9 articles), breast milk is nutritionally unreliable or insufficient (13 articles), body image (8 articles), cost of breast or formula feeding (10 articles), fear (8 articles), health benefits (43 articles), infant attachment (7 articles), knowledge (12 articles), life demands and stress (8 articles), lifestyle (10 articles), not knowing if infant was adequately fed (7 articles), infant age (2 articles), and time and responsibilities (22 articles), confidence (15 articles), formula feeding beliefs (17 articles) which included attitudes (4 articles), convenience and ease of formula feeding (13 articles), and health benefits of formula feeding (6 articles), intention to breastfeed or formula feed (6 articles), introduction to solid foods (2 articles), perseverance (23 articles), previous breastfeeding experience (10 articles). Individual level - health care system domain: healthcare cost (1 article). Interpersonal level - behavioral domain: infant preferences (8 articles), sharing care of infant (12 articles). Interpersonal level - physical/built environment domain: home environment (3 articles), returning to work (30 articles), work environment (23 articles) Interpersonal level - sociocultural environment: exposure to breastfeeding (23 articles), exposure to formula feeding (6 articles), sexualized view of breasts and breastfeeding (7 articles), social support (50 articles) which included social support from partner (27 articles), social support from family (44 articles), and social support from social network (37 articles). Interpersonal level - health care system domain: information and support from health care providers (46 articles). Community level - physical/built environment domain: community resources and support (40 articles) which included breastfeeding resources (31 articles) and community social support (26 articles). Community level - sociocultural environment domain: cultural beliefs, practices, and norms (18 articles). Community level and health care system domain: hospital practices (8 articles), lack of support after hospital discharge (4 articles). Societal level - behavioral domain: maternity leave and breastfeeding laws (3 articles). Societal level - sociocultural environment domain: breastfeeding in public (30 articles), historical context (5 articles). Other combinations of NIMHD levels and domains did not have any themes identified.

| NIMHD Level
NIMHD Domain | Individual | Interpersonal | Community | Societal
Biological | Health issues (10); Physical breastfeeding problems (39)
Behavioral | Breastfeeding beliefs, knowledge, and experiences (57):; - Breastfeeding attitudes (14); - Breastfeeding being convenient or easy (9); - Breast milk is nutritionally unreliable or insufficient (13); - Body image (8); - Cost of breast or formula feeding (10); - Fear (8); - Health benefits (43); - Infant attachment (7); - Knowledge (12); - Life demands and stress (8); - Lifestyle (10); - Not knowing if infant was adequately fed (7); - Infant age (2); - Time and responsibilities (22); Confidence (15); Formula feeding beliefs (17); - Attitudes (4); - Convenience and ease of formula feeding (13); - Health benefits of formula feeding (6); Intention to breastfeed or formula feed (6); Introduction to solid foods (2); Perseverance (23); Previous breastfeeding experience (10) | Infant preferences (8); Sharing care of infant (12) | | Maternity leave and breastfeeding laws (3)
Physical/Built environment | | Home environment (3); Returning to work (30); Work environment (23) | Community resources and support (40):; - Breastfeeding resources (31); - Community social support (26)
Sociocultural environment | | Exposure to breastfeeding (23); Exposure to formula feeding (6); Sexualized view of breasts and breastfeeding (7); Social support (50):; - Social support from partner (27); - Social support from family (44); - Social support from social network (37) | Cultural beliefs practices, and norms (18) | Breastfeeding in public (30); Historical context (5)
Health care system | Cost of hospital lactation services (1) | Information and support from health care providers (46) | Hospital practices (8); Lack of support after hospital discharge (4)

#### Description of the evidence

This rapid review includes 72 articles^72–143^ (from 66 studies) identified themes that may be related to racial and/or ethnic disparities in human milk feeding using qualitative methods (study characteristics and results presented in Appendix 7). Articles with the same or overlapping participants were combined in the description of the evidence and synthesis.^73,74,93,94,101–104,131,132,142,143^ Among these pairs of articles with overlapping participants, only new themes that emerged from the second article were extracted.

Among the 72 qualitative articles, the median sample size was 21 and ranged from 5^128^ to 253.^84^ Sixteen of these articles had sample sizes with 15 or fewer participants,^77,89,95,102,105,108,112–114,117,118,120,128,129,133,138^ 36 articles had sample sizes between 16 and 30 participants,^73,74,78,79,81–83,85,86,88,91,97,98,100,101,103,104,107,110,111,115,116,119,121–125,127,130–132,134,135,139,141^ 11 articles had sample sizes between 30 to 45,^76,87,90,93,99,109,126,136,140,142,143^ and 9 articles had sample sizes between 60 to 253.^72,75,80,84,92,94,96,106,137^

Approximately 60 percent of articles used a theoretical framework.^73,74,77,78,81,83,86–91,94,95,99,101,102,105,108,110–115,117,120,123,124,126,127,130–133,135,139–143^ Eight articles used the Theory of Planned Behavior,^88,90,101,108,112,124,139,140^ seven articles used Black Feminist Theory,^73,74,120,127,135,142,143^ five articles used the Social Cognitive Theory,^102,110,111,131,132^ five articles used the Socioecological Model,^81,83,115,117,133^ and two articles used the Ecological model,^78,112^ One study each used the Family Life Course Development Theory,^73,74^ Integrative Model of Behavior Prediction,^127^ Symbolic Interactionism,^142^ Core Food Security Module,^94^ Conceptual Model for Breastfeeding Behavior,^99^ Developmental Niche Framework,^77^ Factors Influencing Beliefs,^91^ Health Promotion Model,^141^ Individual Net-Benefit Maximization,^126^ Integrative model,^78^ Levels of racism,^113^ Medical Anthropological Framework,^86^ Predicting and Changing Behavior Theory,^105^ Positive Deviance Approach,^95^ PEN-3 Model,^87^ Pragmatic Research Paradigm,^89^ Constructivist Grounded Theory,^123^ Self-efficacy Theory,^130^ and the Theory of Culture Care Diversity and Universality.^114^

##### Population

The studies were conducted with mothers of various races and ethnicities, most commonly including studies with mothers who were exclusively or predominantly African American and/or Black (35 studies from 40 articles),^72–74,78,82–87,89,91,95,99,101–104,106,108,109,113,114,116,119–123,126–133,135,142,143^ or exclusively or predominantly Hispanic (8 studies from 9 articles)^80,93,94,100,105,110,117,118,141^ or Latina (5 studies).^79,92,117,134,140^ Other studies included mothers who were Somali (2 studies),^98,136^ Asian (2 studies),^111,112^ predominantly White,^97^ refugees from Burundi and the Democratic Republic of Congo,^77^ Brazilian,^115^ and Marshallese.^76^ The remaining studies included one study with 56 percent African American and 44 percent Caucasian mothers,^75^ one study with 65 percent Black, 15 percent Asian or Asian American, 15 percent Other, and 5 percent White mothers,^81^ one study with half African American and half African-born mothers,^88^ one study with 60 percent White and 40 percent African American mothers,^90^ one study with a diverse sample including Puerto Rican, West Indian/Jamaican, African American, other ethnic/racial, and White mothers,^96^ one study with half African American and half Puerto Rican mothers,^107^ one study with 65 percent Hispanic mothers, and smaller racial and ethnic groups including White and other mothers,^124^ one study with 60 percent Latina mothers, and smaller racial and ethnic groups including Black, Asian, and White mothers,^125^ one study with 54 percent Hispanic, 31 percent Black, and smaller racial/ethnic groups including Asian, bi-/multiracial/other and White mothers,^137^ one study with 55 percent Somali and 45 percent Mexican mothers,^138^ and one study with 45 percent African American and 34 percent White mothers and smaller racial and ethnic groups including Hispanic and other mothers.^139^ Three studies (from four articles) were conducted with first-time mothers,^73,74,108,127^ and 15 studies (from 17 articles) were conducted with mothers who had low-income,^72,78,80,86,91–96,107,108,125,126,129,131,132^, 6 of which were conducted with mothers who participated in WIC.^95,96,107,108,129,131,132^

Study locations varied across the studies. Eight articles were conducted in New York,^92–94,107,111,112,125,137^ six articles were conducted in Florida,^84,86,110,123,142,143^ five articles each were conducted in Washington D.C.^82,85,106,131,132^ or Ohio,^72,88,91,97,140^ and four articles each were conducted in California,^73–75,83^ Michigan,^90,103,104,133^ or North Carolina.^87,109,113,139^ Three articles each were conducted in Illinois,^75,108,128^ Maryland,^106,126,134^ Massachusetts,^79,115,124^ or Missouri,^101,102,120^ while two articles each were conducted in Georgia,^81,95^ Indiana,^121,122^ South Carolina,^89,119^ Tennessee,^77,116^ Texas,^80,118^ Washington,^100,136^ or Wisconsin.^129,130^ One study each was conducted in Connecticut,^96^ Louisiana,^75^ Minnesota,^138^ Nebraska,^105^ New Jersey,^112^ Pennsylvania,^99^ or Virginia.^78^ The remaining studies took place in the Southeastern United States,^114,117^ the Northeastern United States,^98^ the Southwestern United States,^135^ and the Midwest.^141^ One study did not mention a specific state or location within the United States.^127^

##### Exposures

Forty-five qualitative breastfeeding themes were identified and organized using the NIMHD framework. Due to the subjective nature of the NIMHD framework, as well as the complexity of the themes/factors extracted from the included articles, some themes/factors fit into more than one level-domain cell within the NIMHD framework.

Within the individual level and biological domain, two qualitative factors were examined: physical breastfeeding problems^72,75,78,79,81,84,87,88,90–92,95,96,101,103,105–107,109–112,116,117,119,122,124,126,128,130,132–134,136–141^ and health issues.^78,84,90,95,96,105,112,119,137,141^

Within the individual level and behavioral domain, seven qualitative factor was examined: breastfeeding beliefs, knowledge, and experiences,^74,75,77–81,83,84,86–110,112,114–119,121,122,124,126,128,129,132–136,138–141,143^ confidence,^75,78,88,91,98,115,116,118,124,127,129,132,133,135,141^ formula feeding beliefs,^76,78,79,87,90,92,94,98,101,107,114,115,124,126,128,134,136^ intention to breastfeed or formula feed,^78,90,91,99,119,126^ introduction to solid foods,^105,107^ perseverance,^72,74,75,78,85,88–91,93,96,101,105,107,112,120,125,128,130,133,135,137,141^ and previous breastfeeding experience.^81,86,89,90,95,99,116,128,130,141^

Within the individual level and health care system domain, one qualitative factor was examined: cost of hospital lactation services.^116^

Within the interpersonal level and behavioral domain, two qualitative factors were examined: infant preferences^81,86,89,90,95,99,116,128,130,141^ and sharing care of the infant.^74,76,77,86,88,90,91,98,100,111,134,136^

Within the interpersonal level and physical/built environment domain, three qualitative factors were examined: home environment,^96,103,107^ returning to work,^74–79,84,86,88,90,92,95,96,98,100,101,105,106,112,114–116,124,126,133,134,136,138–140^ and work environment.^74,79,82,83,85–88,95,99–103,108,114,116,122,124,126,131,135,141^

Within the interpersonal level and sociocultural environment domain, three qualitative factors were examined: exposure to breastfeeding^74,81,82,86,88,89,91,95,99,101,107,114,115,117,119–121,126,128,130,135,139,143^ or formula feeding,^87,88,99,101,107,143^ sexualized view of breasts and breastfeeding,^89,91,99,102,107,116,128^ and social support.^74,77–83,88–91,95,96,98–102,105–109,111–121,124,126,127,129,130,132,133,135,136,138–143^

Within the interpersonal level and health care system domain, one qualitative factor was examined: information and support from health care providers.^74,75,78–81,84–86,88–91,95,96,98,99,101–105,107–109,112–116,118,119,121,125,126,128,130,132–139,141^

Within the community level and physical/built environment domain, one qualitative factor were examined: community resources and support,^73,74,77,78,80,81,83–86,88–91,95,96,99,101–103,105,107–109,112,113,115–121,123,129,132,134,135,139,140^ which was subdivided into breastfeeding resources^73,74,77,78,80,81,84–86,88–91,95,99,101,102,107,108,112,113,116–119,121,132,134,135,139,140^ and community social support.^73,74,78,80,81,83,85,86,95,96,99,101,103,105,107–109,115,116,120,121,123,129,132,135,139^

Within the community level and sociocultural environment domain, one qualitative theme was examined: cultural beliefs, practices, and norms.^76,77,88,99,100,107,108,111–113,115–117,135,136,138,140,141^

Within the community level and health care system domain, two qualitative factors were examined: hospital practices^79,84,85,95,107,128,134,137^ and lack of support after discharge.^84,91,128,132^

Within the societal level and behavioral domain, one qualitative factor was examined: maternity leave and breastfeeding laws.^85,86,115^

Within the societal level and sociocultural environment domain, two qualitative factors were examined: breastfeeding in public^74,76–78,82,83,85,90,91,95,99,100,102,104,107–109,114–117,121–123,130,132,135,136,138,140^ and historical context.^85,87,99,116,143^

##### Outcomes

The studies examined human milk feeding experiences, as well as human milk feeding initiation, and duration of any or exclusive human milk feeding.

#### Evidence synthesis

The results of the qualitative studies are presented in Appendix 7. Qualitative themes were organized by NIMHD framework and were categorized as either positive or negative breastfeeding themes. Positive breastfeeding themes referred to themes that facilitated breastfeeding, while negative breastfeeding themes referred to themes that hindered breastfeeding.

##### NIMHD framework: individual level – biological domain

Within the individual level and biological domain, two qualitative factors were examined: physical breastfeeding problems^72,75,78,79,81,84,87,88,90–92,95,96,101,103,105–107,109–112,116,117,119,122,124,126,128,130,132–134,136–141^ and health issues.^78,84,90,95,96,105,112,119,137,141^

Physical breastfeeding problems were an overarching theme in 39 studies,^72,75,78,79,81,84,87,88,90–92,95,96,101,103,105–107,109–112,116,117,119,122,124,126,128,130,132–134,136–141^ all of which were negative breastfeeding themes. Commonly mentioned physical problems that inhibited breastfeeding were insufficient milk supply, latching difficulties, and pain.^72,75,78,79,81,84,87,88,90–92,95,96,101,103,105–107,109–112,116,117,119,122,124,126,128,130,132–134,136–141^ Eighteen of these studies included exclusively or predominantly African American mothers,^72,78,84,87,91,95,101,103,106,109,116,119,122,126,128,130,132,133^ eight included exclusively Hispanic^105,110,117,141^ or exclusively or predominantly Latina^79,92,117,134,140^ mothers, and one study each included exclusively Somali,^136^ Chinese,^111^ and Korean^112^ mothers. The participants of the remaining studies included one study among 56 percent African American and 44 percent Caucasian mothers,^75^ one study among 65 percent Black, 15 percent Asian or Asian American, 15 percent Other, and 5 percent White mothers,^81^ one study among half African American and half African-born mothers,^88^ one study among 60 percent White and 40 percent African American mothers,^90^ one study among a diverse sample including Puerto Rican, West Indian/Jamaican, African American, other ethnic/racial, and White mothers,^96^ one study among half African American and half Puerto Rican mothers,^107^ one study among 65 percent Hispanic mothers, and smaller racial and ethnic groups including White and other mothers,^124^ one study among 54 percent Hispanic, 31 percent Black, and smaller racial and ethnic groups including Asian, bi-/multiracial/other and White mothers,^137^ one study among 55 percent Somali and 45 percent Mexican mothers,^138^ and one study among 45 percent African American, 34 percent White mothers, and smaller racial and ethnic groups including Hispanic and other mothers.^139^

Health issues were an overarching theme in 10 studies,^78,84,90,95,96,105,112,119,137,141^ with 2 studies reporting positive breastfeeding themes,^78,95^ and 9 studies reporting negative breastfeeding themes.^84,90,95,96,105,112,119,137,141^ Among the two studies that reported positive breastfeeding themes,^78,95^ mothers in both studies mentioned that their infants experienced digestion issues with formula. These studies were among exclusively African American mothers.^78,95^ Among the nine studies that reported negative breastfeeding themes,^84,90,95,96,105,112,119,137,141^ mothers mentioned issues such as they were sick or were taking medication, or that their infant had health issues, such as staying in the NICU or potential allergy. Three of these studies were among exclusively African American mothers,^84,95,119^ two were among exclusively Hispanic mothers,^105,141^ one study was among 60 percent White and 40 percent African American mothers,^90^ one study was among exclusively Korean mothers,^112^ one study included a diverse sample including Puerto Rican, West Indian/Jamaican, African American, other ethnic/racial, and White mothers,^96^ and one study was among 54 percent Hispanic, 31 percent Black, and smaller racial and ethnic groups including Asian, bi-/multiracial/other and White mothers.^137^

##### NIMHD framework: individual level – behavioral domain

Within the individual level and behavioral domain, the following qualitative factors were examined: breastfeeding beliefs, knowledge, and experiences, formula feeding beliefs, confidence, intention to breastfeed or formula feed, introduction to solid foods, perseverance, and previous BF experience.

##### Breastfeeding beliefs, knowledge, and experiences

Breastfeeding beliefs, knowledge, and experiences was an overarching theme in 57 studies,^74,75,77–81,83,84,86–110,112,114–119,121,122,124,126,128,129,132–136,138–141,143^ which were subdivided into the following categories: breastfeeding attitudes,^78,79,84,87,92,96,98,99,110,112,124,126,138,141^ breastfeeding being convenient or easy,^88,90,101,103,108,110,132,135,140^ breast milk is nutritionally unreliable or insufficient,^75,78,87,94,98,107,108,115,116,118,122,124,134^ body image,^79,87,96,100,106,121,138,140^ cost,^78,81,83,88,91,94,102,105,108,135^ fear,^78,84,88,91,116,124,134,138^ health benefits,^74,79–81,83,84,87–92,95,99–101,103–105,107,108,110,112,114,115,117–119,121,124,126,128,129,132–136,138–141,143^ infant attachment,^78,83,86,96,99,114,132^ knowledge,^80,81,90,91,95,99,106,107,116,132,136,138^ life demands and stress,^93,94,97,103,104,124,126,138^ lifestyle,^78,84,86,90,106,108,109,121,134,143^ not knowing if infant was adequately fed,^84,90,91,101,115,136,143^ infant age,^96,105^ and time and responsibilities.^75,77,83,84,86,88,91,93,95,96,99,101,103,105,107,109,110,116,122,126,132,136^

Breastfeeding attitudes was an overarching theme within breastfeeding beliefs, knowledge and experiences in 14 studies,^78,79,84,87,92,96,98,99,110,112,124,126,138,141^ with 7 reporting positive breastfeeding themes^79,96,99,112,124,126,141^ and 10 reporting negative breastfeeding themes.^78,79,84,87,92,96,98,99,110,138^ Among the seven studies reporting positive breastfeeding themes,^79,96,99,112,124,126,141^ mothers mentioned having positive attitudes towards breastfeeding, such as that breastfeeding is natural or important. Two of these studies were among exclusively or predominantly African American mothers,^99,126^ two were among exclusively Hispanic^141^ or predominantly Latina^79^ mothers, one study was among exclusively Korean mothers,^112^ one study included a diverse sample including Puerto Rican, West Indian/Jamaican, African American, other ethnic/racial, and White mothers,^96^ and one study was among 65 percent Hispanic mothers, and smaller racial and ethnic groups including White and other mothers.^124^ Among the 10 studies reporting negative breastfeeding themes,^78,79,84,87,92,96,98,99,110,138^ mothers mentioned themes such as feeling embarrassed, uncomfortable, and ambivalent about breastfeeding. Four of these studies were among exclusively African American mothers,^78,84,87,99^ two were among exclusively Hispanic^110^ or predominantly Latina^92^ mothers, one study was among exclusively Somali mothers,^98^ one study included a diverse sample including Puerto Rican, West Indian/Jamaican, African American, other ethnic/racial, and White mothers,^96^ and one study was among 55 percent Somali and 45 percent Mexican mothers.^138^

Breastfeeding being convenient or easy (or not being convenient or easy) was an overarching theme within breastfeeding beliefs, knowledge and experiences in nine studies,^88,90,101,103,108,110,132,135,140^ with eight studies reporting positive breastfeeding themes^88,90,101,103,108,132,135,140^ and two studies reporting negative breastfeeding themes.^110,132^ Among the eight studies reporting positive breastfeeding themes,^88,90,101,103,108,132,135,140^ mothers mentioned that breastfeeding was convenient and easy, giving examples such as not having to prepare bottles and making night feedings easier. Five of these studies were among African American mothers,^101,103,108,132,135^ one was among exclusively Latina mothers,^140^ one study was among half African American and half African-born mothers,^88^ and one study was among 60 percent White and 40 percent African American mothers.^90^ Among the two studies reporting negative breastfeeding themes,^110,132^ mothers mentioned that there was a misconception that breastfeeding was easy. One study each was among exclusively African American mothers,^132^ and exclusively Hispanic mothers.^110^

Breast milk is nutritionally unreliable or insufficient was an overarching theme within breastfeeding beliefs, knowledge and experiences in 13 studies,^75,78,87,94,98,107,108,115,116,118,122,124,134^ all of which were negative breastfeeding themes. Mothers mentioned themes such as that breast milk was insufficient, inadequate, or did not provide enough nutrients for their baby, or believing that medications, negative emotions, or poor diet lead to a low quality breast milk.^75,78,87,94,98,107,108,115,116,118,122,124,134^ Five of these studies were among exclusively African American mothers,^78,87,108,116,121^ three studies were among exclusively or predominantly Hispanic^94,118^ or exclusively Latina^134^ mothers, one study each was among exclusively Somali^98^ and exclusively Brazilian^115^ mothers, one study was among 56 percent African American and 44 percent Caucasian mothers,^75^ one study was among half African American and half Puerto Rican mothers,^107^ one study was among 65 percent Hispanic mothers, and smaller racial and ethnic groups including White and other mothers.^124^

Body image was an overarching theme within breastfeeding beliefs, knowledge and experiences in eight studies,^79,87,96,100,106,121,138,140^ all of which were negative breastfeeding themes. Mothers mentioned that breastfeeding would affect their breast’s appearance, such as causing drooping, sagging, or changes in size. One study noted that undesirable physical changes were primarily mentioned among younger women.^100^ Three of these studies were conducted exclusively with African American women,^87,106,121^ three were conducted with exclusively Hispanic^100^ or exclusively or predominantly Latina^79,140^ women, one study included a diverse sample including Puerto Rican, West Indian/Jamaican, African American, other ethnic/racial, and White mothers,^96^ one study was among 55 percent Somali and 45 percent Mexican mothers.^138^

Cost of breast or formula feeding was an overarching theme within breastfeeding beliefs, knowledge and experiences in 10 studies,^78,81,83,88,91,94,102,105,108,135^ with 9 studies reporting positive breastfeeding themes,^78,81,88,91,94,102,105,108,135^ and with 3 studies reporting negative breastfeeding themes.^83,88,108^ Among the nine studies reporting positive breastfeeding themes,^78,81,88,91,94,102,105,108,135^ mothers indicated that formula was expensive and that it was less expensive to breastfeed than to formula feed. Five of these studies were among exclusively African American mothers,^78,91,101,108,135^ two were among exclusively Hispanic mothers,^94,105^ and one study was among half African American and half African-born mothers.^88^ Among the three studies reporting negative breastfeeding themes,^83,88,108^ mothers in two studies mentioned costs involved with breastfeeding,^88,108^ although one study highlighted that the lower cost of breastfeeding may suggest that breastfeeding is lower quality than more expensive formula.^83^ Two of these studies were among exclusively or predominantly African American mothers,^83,108^ one study was among half African American and half African-born mothers,^88^ and one study was among 65 percent Black, 15 percent Asian or Asian American, 15 percent Other, and 5 percent White mothers.^81^

Fear was an overarching theme within breastfeeding beliefs, knowledge and experiences in eight studies,^78,84,88,91,116,124,134,138^ all of which were negative breastfeeding themes. Mothers primarily indicated a fear of pain with breastfeeding, with fewer studies mentioning other fears such as fear of insufficient milk supply and fear of change.^78,84,88,91,116,124,134,138^ Four of these studies were among exclusively African American mothers,^78,84,91,116^ one was among exclusively Latina mothers,^134^ one study was among half African American and half African-born mothers,^88^ one study was among 65 percent Hispanic mothers, and smaller racial and ethnic groups including White and other mothers,^124^ and one study was among 55 percent Somali and 45 percent Mexican mothers.^138^

Health benefits was an overarching theme within breastfeeding beliefs, knowledge and experiences in 42 studies (43 articles),^74,79–81,83,84,87–92,95,99–101,103–105,107,108,110,112,114,115,117–119,121,124,126,128,129,132–136,138–141,143^ with 42 studies (43 articles) reporting positive breastfeeding themes^74,79–81,83,84,87–92,95,99–101,103–105,107,108,110,112,114,115,117–119,121,124,126,128,129,132–136,138–141,143^ and 1 study reporting a negative breastfeeding theme.^114^ Among the 42 studies reporting positive breastfeeding themes,^74,79–81,83,84,87–92,95,99–101,103–105,107,108,110,112,114,115,117–119,121,124,126,128,129,132–136,138–141,143^ mothers indicated that there are health benefits of breastfeeding for the mother and infant and that breastfeeding is healthier. Some of the health benefits mentioned included emotional benefits from bonding, preventing illnesses in the infant, and weight loss for the mother. Twenty-one of these studies were among exclusive or predominantly African American mothers,^74,83,84,87,89,91,95,99,101,103,104,108,114,119,121,126,128,132,133,135,143^ 11 of these studies were among exclusively or predominantly Hispanic^80,100,105,110,117,118,141^ or exclusively or predominantly Latina^79,92,117,134,140^ mothers, one study was among exclusively Somali mothers, one study was among exclusively Korean mothers,^112^ and one study was among exclusively Brazilian mothers.^115^ The remaining studies included one study among 65 percent Black, 15 percent Asian or Asian American, 15 percent Other, and 5 percent White mothers,^81^ one study among half African American and half African-born mothers,^88^ one study among 60 percent White and 40 percent African American mothers,^90^ one study among half African American and half Puerto Rican mothers,^107^ one study among 65 percent Hispanic mothers, and smaller racial and ethnic groups including White and other mothers,^124^ one study among 55 percent Somali and 45 percent Mexican mothers,^138^ and one study among 45 percent African American and 34 percent White mothers and smaller racial and ethnic groups including Hispanic and other mothers.^139^ In the one study reporting a negative breastfeeding theme,^114^ mothers were concerned that milk would be harmful, such as rotting the teeth of their infants. This study was among exclusively African American mothers.^114^

Infant attachment was a negative breastfeeding theme within breastfeeding beliefs, knowledge, and experiences in seven studies,^78,83,86,96,99,114,132^ providing it as a reason to stop breastfeeding. Mothers were concerned that breastfeeding for too long of a duration would “spoil” the baby or lead to over-attachment. Six of these studies were conducted with exclusively or predominantly African American mothers^78,83,86,99,114,132^ and one study^96^ with a mixed sample with mainly Puerto Rican, West Indian/Jamaican, and African American mothers.

Knowledge was an overarching theme within breastfeeding beliefs, knowledge, and experiences in 12 studies,^80,81,90,91,95,99,106,107,116,132,136,138^ with 7 studies reporting positive breastfeeding themes^80,81,90,95,106,116,136^ and 8 studies reporting negative breastfeeding themes.^90,91,99,106,107,136,138^ Among the seven studies reporting positive breastfeeding themes,^80,81,90,95,106,116,136^ mothers mentioned knowledge of how to latch, increase milk supply, and resolve breastfeeding issues, and knowledge of strategies to facilitate or make breastfeeding easier. Three of these studies were among exclusively African American mothers,^95,106,116^ one study was among majority Hispanic mothers,^80^ one study was among exclusively Somali mothers,^136^ one study was among 65 percent Black, 15 percent Asian or Asian American, 15 percent Other, and 5 percent White mothers,^81^ and one study was among 60 percent White and 40 percent African American mothers.^90^ Among the eight studies reporting negative breastfeeding themes,^90,91,99,106,107,136,138^ mothers indicated a lack of knowledge generally and on a variety of topics, such as breastfeeding dynamics (e.g., how to latch) and nipple sanitization, and acknowledged a lack of breastfeeding education. Four of these studies were among exclusively African American mothers,^91,99,106,132^ one study was among exclusively Somali mothers,^136^ one study was among 60 percent White and 40 percent African American mothers,^90^ one study included half African American and half Puerto Rican mothers,^107^ and one study was among 55 percent Somali and 45 percent Mexican mothers.^138^

Life demands and stress was an overarching theme within breastfeeding beliefs, knowledge, and experiences in six studies (eight articles),^93,94,97,103,104,124,126,138^ all of which were negative breastfeeding themes. These negative breastfeeding themes related to a variety of life demands and stresses such as stress due to mental health, home- and family-related stress and hardship, and poverty.^93,94,97,103,104,124,126,138^ Examples of family-related stressors included loss of a parent, family members who were abusive or struggling with drug addiction, caring for multiple family members, and domestic violence. Home-related stressors included experiencing homelessness, experiencing poverty, having fewer resources, and having competing life demands. Three of these studies were conducted predominantly or exclusively with African American women,^103,104,126^ one study (two articles) was conducted exclusively among Hispanic mothers,^93,94^ one study was among predominantly White mothers,^97^ one study was among 65 percent Hispanic mothers, and smaller racial and ethnic groups including White and other mothers,^124^ and one study was among 55 percent Somali and 45 percent Mexican mothers.^138^ The study with majority White mothers reported a gap in mental health (depression and anxiety) knowledge, with mental health issues being more prominent among African American and Hispanic mothers than White mothers.^97^

Lifestyle impacting breastfeeding or beliefs about lifestyles was an overarching theme within breastfeeding beliefs, knowledge, and experiences in 10 studies,^78,84,86,90,106,108,109,121,134,143^ with 1 study reporting a positive breastfeeding theme^90^ and 9 studies reporting negative breastfeeding themes.^78,84,86,106,108,109,121,134,143^ In the one positive breastfeeding theme,^90^ White and African American mothers mentioned that they altered their own diet if their child had trouble breastfeeding. This study was among 60 percent White and 40 percent African American mothers.^90^ Among the nine studies reporting negative breastfeeding themes,^78,84,86,106,108,109,121,134,143^ mothers mentioned lifestyle factors that they believed were incompatible with breastfeeding, including smoking, alcohol, diet, medications, and wanting freedom. Eight of these studies were exclusively among African American mothers,^78,84,86,106,108,109,121,143^ and one study sample was exclusively Latina mothers.^134^

Not knowing if infant was adequately fed was an overarching theme within breastfeeding beliefs, knowledge, and experiences in seven studies,^84,90,91,101,115,136,143^ all of which were negative breastfeeding themes. Mothers indicated uncertainty about whether their infant was consuming enough breast milk or was adequately fed.^84,90,91,101,115,136,143^ Four of these studies were exclusively among African American mothers,^84,91,101,143^ one study was exclusively among Somali mothers,^136^ one study was exclusively among Brazilian mothers,^115^ and one study was among 60 percent White and 40 percent African American mothers.^90^

Infant age was a negative breastfeeding theme within breastfeeding beliefs, knowledge, and experiences in two studies,^96,105^ with mothers indicating that the infant was old enough to stop breastfeeding or growing old. One study was exclusively among Hispanic mothers^105^ and one study included a diverse sample including Puerto Rican, West Indian/Jamaican, African American, other ethnic/racial, and White mothers.^96^

Time and responsibilities was an overarching theme within breastfeeding beliefs, knowledge, and experiences in 22 studies,^75,77,83,84,86,88,91,93,95,96,99,101,103,105,107,109,110,116,122,126,132,136^ all of which reported negative breastfeeding themes, although one study also reported 1 positive breastfeeding theme.^95^ In the one study reporting a positive breastfeeding theme, pumping was mentioned as a strategy to incorporate breastfeeding into a busy schedule in an exclusive sample of African American women.^95^ Among the 22 studies reporting negative breastfeeding themes,^75,77,83,84,86,88,91,93,95,96,99,101,103,105,107,109,110,116,122,126,132,136^ mothers indicated that breastfeeding is time consuming and that they did not have enough time to breastfeed due to busy schedules or other responsibilities such as other children and work.^75,77,83,84,86,88,91,93,95,96,99,101,103,105,107,109,110,116,122,126,132,136^ Thirteen of these studies were exclusively or predominantly among African American mothers,^83,84,86,91,95,99,101,103,109,116,122,126,132^ three were exclusively among Hispanic mothers,^93,105,110^ one study was among exclusively Somali mothers,^136^ one study included 56 percent African American and 44 percent Caucasian mothers,^75^ one study was among half Burundian and half Congolese mothers,^77^ one study was among half African American and half African-born mothers,^88^ one study included a diverse sample including Puerto Rican, West Indian/Jamaican, African American, other ethnic/racial, and White mothers,^96^ and one study included half African American and half Puerto Rican mothers.^107^

###### Formula Feeding Beliefs

Formula feeding beliefs was an overarching theme in 17 studies,^76,78,79,87,90,92,94,98,101,107,114,115,124,126,128,134,136^ which were subdivided into three categories: attitudes,^78,79,87,90^ convenience and ease of formula feeding,^79,87,90,94,98,101,107,114,124,126,128,134,136^ and health benefits of formula.^76,79,92,107,115,136^

Attitudes was an overarching theme within formula feeding beliefs in four studies,^78,79,87,90^ with three studies reporting positive breastfeeding themes^78,79,90^ and three studies reporting negative breastfeeding themes.^78,87,90^ Among the three studies that reported positive breastfeeding themes,^78,79,90^ mothers mentioned having negative attitudes or beliefs about formula. One study was exclusively among African American mothers,^78^ one study was among predominantly Latina mothers,^79^ and one study was among 60 percent White and 40 percent African American mothers.^90^ Among the three studies that reported negative breastfeeding themes,^78,87,90^ mothers mentioned that formula was normal or familiar to them or that they did not have strong preferences for breastfeeding over formula feeding. Two of these studies were exclusively among African American mothers^78,87^ and one study was among 60 percent White and 40 percent African American mothers.^90^

Convenience and ease of formula feeding was an overarching theme within formula feeding beliefs in 13 studies,^79,87,90,94,98,101,107,114,124,126,128,134,136^ with 1 study reporting a positive breastfeeding theme94 and 12 studies reporting negative breastfeeding themes.^79,87,90,98,101,107,114,124,126,128,134,136^ In the one study that reported the positive breastfeeding theme, mothers mentioned that formula was not always available in a study exclusively among Hispanic mothers.^94^ Among the 12 studies reporting negative breastfeeding themes,^79,87,90,98,101,107,114,124,126,128,134,136^ mothers mentioned that formula was easier or more convenient than breastfeeding, particularly when returning to work. Five of these studies were exclusively or predominantly among African American mothers,^87,101,114,126,128^ two were exclusively or predominantly among Latina mothers,^79,134^ two were exclusively among Somali mothers,^98,136^ one study was among 60 percent White and 40 percent African American mothers,^90^ one study included half African American and half Puerto Rican mothers,^107^ and one study was among 65 percent Hispanic mothers, and smaller racial and ethnic groups including White and other mothers.^124^

Health benefits of formula feeding was an overarching theme within formula feeding beliefs in six studies,^76,79,92,107,115,136^ all of which were negative breastfeeding themes. Mothers mentioned themes such as that formula helped with infant growth, kept infants full, and helped infants sleep through the night.^76,79,92,107,115,136^ Two of these studies were among predominantly Latina mothers,^79,92^ one study was among exclusively Somali mothers,^136^ one study was among exclusively Marshallese mothers,^76^ one study was among exclusively Brazilian mothers,^115^ and one study included half African American and half Puerto Rican mothers.^107^

###### Other factors

Confidence or a lack of confidence was an overarching theme in 15 studies,^75,78,88,91,98,115,116,118,124,127,129,132,133,135,141^ with 10 studies reporting positive breastfeeding themes^78,91,98,115,118,127,132,133,135,141^ and 10 studies reporting negative breastfeeding themes.^75,78,88,91,116,124,129,132,133,141^ Among the 10 studies reporting positive breastfeeding themes,^78,91,98,115,118,127,132,133,135,141^ participants mentioned breastfeeding self-efficacy, and that successful breastfeeding increased their self-confidence and sense of accomplishment. Six of these studies were exclusively among African American mothers,^78,91,127,132,133,135^ two were among exclusively or majority Hispanic mothers,^118,141^ one study each was among exclusively Somali^98^ and exclusively Brazilian mothers.^115^ Among the 10 studies reporting negative breastfeeding themes,^75,78,88,91,116,124,129,132,133,141^ mothers indicated low confidence or self-efficacy, including a lack of confidence or self-efficacy about dealing with breastfeeding discomfort and challenges. Six of these studies were among exclusively African American mothers, one was among exclusively Hispanic mothers,^141^ one study included 56 percent African American and 44 percent Caucasian mothers,^75^ one study was among half African American and half African-born mothers,^88^ and one study was among 65 percent Hispanic mothers, and smaller racial and ethnic groups including White and other mothers.^124^

Intention to breastfeed or formula feed was an overarching theme in six studies,^78,90,91,99,119,126^ with six studies reporting positive breastfeeding themes^78,90,91,99,119,126^ and two studies reporting negative breastfeeding themes.^78,90^ Among the six studies reporting positive breastfeeding themes,^78,90,91,99,119,126^ mothers indicated an intention or desire to breastfeed. Five of these studies were among exclusively or predominantly African American mothers,^78,91,99,119,126^ and one study was among 60 percent White and 40 percent African American mothers.^90^ Among the two studies reporting negative breastfeeding themes,^78,90^ mothers in one study mentioned a prenatal intention to formula feed,^78^ while mothers in the other study mentioned intending to breastfeed but encountering challenges with breastfeeding.^90^ One study was exclusively among African American mothers^78^ and one study was among 60 percent White and 40 percent African American mothers.^90^

Introduction to solid foods was a negative breastfeeding theme in two studies,^105,107^ given as a reason to stop or slow down breastfeeding. Mothers indicated numerous reasons to introduce solid foods, including a sign of advanced development, adding cereal 2 days after birth to help the baby sleep, and formula lasting longer with cereal, which led to short breastfeeding durations.^105,107^ One study was among exclusively Hispanic mothers^105^ and one study included half African American and half Puerto Rican mothers.^107^

Perseverance was an overarching theme in 23 studies,^72,74,75,78,85,88–91,93,96,101,105,107,112,120,125,128,130,133,135,137,141^ with 22 studies reporting positive breastfeeding themes^72,74,75,78,85,88–91,93,101,105,107,112,120,125,128,130,133,135,137,141^ and 5 studies reporting negative breastfeeding themes.^75,96,101,112,130^ Among the 22 studies reporting positive breastfeeding themes,^72,74,75,78,85,88–91,93,101,105,107,112,120,125,128,130,133,135,137,141^ mothers indicated persistence and perseverance when encountering problems, such as overcoming pain and disregarding negative comments about breastfeeding from others. Mothers also mentioned that breastfeeding was their decision and that they were motivated to breastfeed. Twelve of these studies were among exclusively or predominantly African American mothers,^72,74,78,85,89,91,101,120,128,130,133,135^ three were among exclusively Hispanic mothers,^93,105,141^ one study was among exclusively Korean mothers,^112^ one study included 56 percent African American and 44 percent Caucasian mothers,^75^ one study was among half African American and half African-born mothers,^88^ one study was among 60 percent White and 40 percent African American mothers,^90^ one study included half African American and half Puerto Rican mothers,^107^ one study was among 60 percent Latina mothers, and smaller racial and ethnic groups including Black, Asian, and White mothers,^125^ and one study was among 54 percent Hispanic, 31 percent Black, and smaller racial and ethnic groups including Asian, bi-/multiracial/other and White mothers.^137^ Among the five studies reporting negative breastfeeding themes,^75,96,101,112,130^ mothers mentioned themes such as giving up when encountering breastfeeding problems or challenges, not seeking support, and feeling overwhelmed when starting breastfeeding. Two of these studies were among exclusively African American mothers,^101,130^ one study was among exclusively Korean mothers,^112^ one study included 56 percent African American and 44 percent Caucasian mothers,^75^ and one study included a diverse sample including Puerto Rican, West Indian/Jamaican, African American, other ethnic/racial, and White mothers.^96^

Previous breastfeeding experience was an overarching theme in 10 studies,^81,86,89,90,95,99,116,128,130,141^ with 10 studies reporting positive breastfeeding themes^81,86,89,90,95,99,116,128,130,141^ and 1 study reporting a negative breastfeeding theme.^130^ Among the 10 positive breastfeeding themes,^81,86,89,90,95,99,116,128,130,141^ mothers mentioned the positive impact of having successful previous breastfeeding experiences. Seven of these studies were exclusively among African American mothers,^86,89,95,99,116,128,130^ one was exclusively among Hispanic mothers,^141^ one study was among 65 percent Black, 15 percent Asian or Asian American, 15 percent Other, and 5 percent White mothers,^81^ and one study was among 60 percent White and 40 percent African American mothers.^90^ The one negative breastfeeding theme related to mothers having previous attempts at breastfeeding which were unsuccessful, which was mentioned among formula feeding mothers.^130^ This study was exclusively among African American mothers.^130^

##### NIMHD framework: individual level – health care system domain

Within the individual level and health care system domain, one qualitative factor was examined: cost of hospital lactation services.^116^

Cost of hospital lactation services was a negative breastfeeding theme in a study exclusively among African American mothers who indicated that the cost of follow-up with an in-patient lactation consultant was costly, which deterred the mother to receive help with breastfeeding after encountering a physical breastfeeding problem.^116^

##### NIMHD framework: interpersonal level – behavioral domain

Within the interpersonal level and behavioral domain, two qualitative factors were examined: infant preferences^81,86,89,90,95,99,116,128,130,141^ and sharing care of the infant.^74,76,77,86,88,90,91,98,100,111,134,136^

Infant preferences was an overarching theme in eight studies,^81,86,89,90,95,99,116,128,130,141^ with one study reporting a positive breastfeeding theme,^141^ and seven studies reporting negative breastfeeding themes.^81,86,89,90,95,99,116,128,130^ In the one positive breastfeeding theme, mothers mentioned that breastfeeding was preferred by and more satisfying for their infants compared to formula.^141^ This study was among exclusively Hispanic mothers.^141^ Among the seven studies reporting negative breastfeeding themes,^81,86,89,90,95,99,116,128,130^ mothers indicated that that their baby preferred bottles or formula to the breast or breastfeeding, and that their baby rejected the breast. Three of these studies were among exclusively or predominantly Latina mothers,^79,92,134^ one was among exclusively African American mothers,^86^ one study included 56 percent African American and 44 percent Caucasian mothers,^75^ one study included a diverse sample including Puerto Rican, West Indian/Jamaican, African American, other ethnic/racial, and White mothers,^96^ and one study included half African American and half Puerto Rican mothers.^107^

Sharing care of infant was an overarching theme in 12 studies,^74,76,77,86,88,90,91,98,100,111,134,136^ all of which were negative breastfeeding themes. Mothers mentioned that it would be harder for other caregivers to feed the child, such as when returning to work, if breastfeeding instead of formula feeding.^74,76,77,86,88,90,91,98,100,111,134,136^ Three of these studies were among exclusively African American mothers,^74,86,91^ two were among exclusively Hispanic^100^ or exclusively Latina^134^ mothers, two studies were among exclusively Somali mothers,^98,136^ one study was among exclusively Marshallese mothers,^76^, one study was among exclusively Chinese mothers,^111^ one study was among half Burundian and half Congolese mothers,^77^ one study was among half African American and half African-born mothers,^88^ and one study was among 60 percent White and 40 percent African American mothers.^90^

##### NIMHD framework: interpersonal level – physical/built environment domain

Within the interpersonal level and physical/built environment domain, three qualitative factors were examined: home environment,^96,103,107^ returning to work,^74–79,84,86,88,90,92,95,96,98,100,101,105,106,112,114–116,124,126,133,134,136,138–140^ and work environment.^74,79,82,83,85–88,95,99–103,108,114,116,122,124,126,131,135,141^

Home environment was an overarching theme in three studies,^96,103,107^ with one positive breastfeeding theme,^107^ and three studies reporting negative breastfeeding themes.^96,103,107^ In the one positive breastfeeding theme, having a private space at home encouraged breastfeeding.^107^ This study included half African American and half Puerto Rican mothers.^107^ Among the three studies reporting negative breastfeeding themes,^96,103,107^ mothers mentioned that a lack of privacy, lack of adequate housing, and desire to breastfeed in private (such as in a bedroom) inhibited breastfeeding. One study was among exclusively African American mothers,^103^ one study included a diverse sample including Puerto Rican, West Indian/Jamaican, African American, other ethnic/racial, and White mothers,^96^ and one study included half African American and half Puerto Rican mothers.^107^

Returning to work was an overarching theme in 30 studies,^74–79,84,86,88,90,92,95,96,98,100,101,105,106,112,114–116,124,126,133,134,136,138–140^ with 2 studies reporting positive breastfeeding themes,^95,133^ and 28 studies reporting negative breastfeeding themes.^74–79,84,86,88,90,92,96,98,100,101,105,106,112,114–116,124,126,134,136,138–140^ Among the two positive breastfeeding themes,^95,133^ mothers mentioned that being able to pump at work and being a stay-at-home mother helped breastfeeding. Both of these studies were among exclusively African American mothers.^95,133^ Among the 28 studies reporting negative breastfeeding themes,^74–79,84,86,88,90,92,96,98,100,101,105,106,112,114–116,124,126,134,136,138–140^ mothers mentioned that returning to work or school was a barrier to breastfeeding, with some studies reporting that formula feeding was easier for this transition and that returning to work led to insufficient milk supply. Nine of these studies were among exclusively or predominantly African American mothers,^74,78,84,86,101,106,114,116,126^ six were among exclusively or predominantly Hispanic^100,105^ or Latina^79,92,134,140^ mothers, two were among exclusively Somali mothers,^98,136^ one study was among Korean mothers,^112^ one study was among exclusively Brazilian mothers,^115^ and one study was among exclusively Marshallese mothers.^76^ The remaining studies included one study with a diverse sample including Puerto Rican, West Indian/Jamaican, African American, other ethnic/racial, and White mothers,^96^ one study among 60 percent White and 40 percent African American mothers,^90^ one study among 45 percent African American and 34 percent White mothers and smaller racial and ethnic groups including Hispanic and other mothers,^139^ one study among half African American and half African-born mothers,^88^ one study among 56 percent African American and 44 percent Caucasian mothers,^75^ one study among 60 percent Latina mothers, and smaller racial and ethnic groups including Black, Asian, and White mothers,^125^ one study among half Burundian and half Congolese mothers,^77^ and one study among 55 percent Somali and 45 percent Mexican mothers.^138^

Work environment was an overarching theme in 22 studies (23 articles),^74,79,82,83,85–88,95,99–103,108,114,116,122,124,126,131,135,141^ with 10 studies reporting positive breastfeeding themes,^79,82,88,95,99,101,124,131,135,141^ and 19 studies reporting negative breastfeeding themes.^74,79,82,83,85–88,100,102,103,108,114,116,122,126,131,135,141^ Among the 10 studies reporting positive breastfeeding themes,^79,82,88,95,99,101,124,131,135,141^ mothers mentioned that having environmental accommodations (e.g., lactation room, nursing station, fridge), time to pump, and supportive employers and coworkers helped to continue breastfeeding after returning to work. Six of these articles were among exclusively or predominantly African American mothers,^82,95,99,101,131,135^ two were among exclusively Hispanic^141^ or predominantly Latina^79^ mothers, one study was among half African American and half African-born mothers,^88^ and one study with 65 percent Hispanic mothers, and smaller racial and ethnic groups including White and other mothers.^124^ Among the 19 studies reporting negative breastfeeding themes,^74,79,82,83,85–88,100,102,103,108,114,116,122,126,131,135,141^ mothers reported facing challenges when at work, such as a lack of accommodations (e.g., suitable private locations, places to store milk) and time for pumping, fears about losing their job, and not having supportive employers and coworkers. Fifteen of these studies were among exclusively or predominantly African American mothers,^74,82,83,85–87,102,103,108,114,116,121,126,131,135^ 3 were among exclusively Hispanic^100,141^ or predominantly Latina^79^ mothers, and one study was among half African American and half African-born mothers.^88^

##### NIMHD framework: interpersonal level – sociocultural environment domain

Within the interpersonal level and sociocultural environment domain, three qualitative factors were examined: exposure to breastfeeding^74,81,82,86,88,89,91,95,99,101,107,114,115,117,119–121,126,128,130,135,139,143^ or formula feeding,^87,88,99,101,107,143^ sexualized view of breasts and breastfeeding,^89,91,99,102,107,116,128^ and social support.^74,77–83,88–91,95,96,98–102,105–109,111–121,124,126,127,129,130,132,133,135,136,138–143^

Exposure to breastfeeding was an overarching theme in 23 studies,^74,81,82,86,88,89,91,95,99,101,107,114,115,117,119–121,126,128,130,135,139,143^ with 18 studies reporting positive breastfeeding themes,^74,81,82,86,88,91,95,99,101,107,114,117,120,126,128,135,139,143^ and 13 studies reporting negative breastfeeding themes.^74,86,89,95,99,101,107,114,115,119,121,130,139^ Among the 18 studies reporting positive breastfeeding themes,^74,81,82,86,88,91,95,99,101,107,114,117,120,126,128,135,139,143^ mothers indicated being exposed to breastfeeding through their family and friends, including having a family history of breastfeeding, and that breastfeeding was normal in their social network. Among the 13 studies reporting negative breastfeeding themes,^74,86,89,95,99,101,107,114,115,119,121,130,139^ mothers indicated that they had a lack of exposure to breastfeeding from their friends and family, a lack of breastfeeding role models, and that breastfeeding was not a social norm. Ten of these studies were among exclusively African American mothers,^74,86,89,95,99,101,114,119,121,130^ one study was among exclusively Brazilian mothers,^115^ 1 study included half African American and half Puerto Rican mothers,^107^ and 1 study included 45 percent African American and 34 percent White mothers and smaller racial and ethnic groups including Hispanic and other mothers.^139^

Exposure to formula feeding was an overarching theme in six studies,^87,88,99,101,107,143^ all of which were negative breastfeeding themes. Mothers indicated that formula was normal in their family and that they were exposed to formula feeding throughout life, such as by observing family members formula feeding.^87,88,99,101,107,143^ Four of these studies were among exclusively African American mothers,^87,99,101,143^ one study was among half African American and half African-born mothers,^88^ and one study included half African American and half Puerto Rican mothers.^107^

Sexualized view of breasts and breastfeeding was an overarching theme in seven studies,^89,91,99,102,107,116,128^ all of which were negative. Mothers mentioned believing that others (such as friends or their partner) had sexualized views of breasts or breastfeeding, which negatively impacted their desire to breastfeed. Six of these studies were with exclusively African American mothers,^89,91,99,102,116,128^ and one study^107^ included 50 percent African American and 50 percent Puerto Rican mothers.

Social support was an overarching theme in 48 studies (50 articles),^74,77–83,88–91,95,96,98–102,105–109,111–121,124,126,127,129,130,132,133,135,136,138–143^ which was subdivided into social support from partner (27 studies),^78,79,81–83,88,89,91,95,96,99,100,102,106–108,111,114,116,124,126,129,130,132,135,140,141^ social support from family other than their partner (42 studies, 44 articles),^74,77,79,80,82,83,88–91,95,96,98–102,105–107,109,111–117,119–121,124,126,129,130,132,135,136,138–143^ and social support from social network other than family and partner (36 studies, 37 articles).^74,78–83,88,90,91,99,101,102,106–109,112–118,120,121,124,126,127,129,130,132,133,135,136,139,141^

Social support from partner was an overarching theme in 27 studies,^78,79,81–83,88,89,91,95,96,99,100,102,106–108,111,114,116,124,126,129,130,132,135,140,141^ with 21 studies reporting positive breastfeeding themes^79,81–83,88,89,91,95,99,100,102,107,111,116,124,126,130,132,135,140,141^ and 10 studies reporting negative breastfeeding themes.^78,82,91,96,99,106,108,114,116,129^ Among the 21 studies reporting positive breastfeeding themes,^79,81–83,88,89,91,95,99,100,102,107,111,116,124,126,130,132,135,140,141^ mothers frequently indicated that their partner was supportive of breastfeeding and provided encouragement and social support. Twelve of these studies were among exclusively or predominantly African American mothers,^82,83,89,91,95,99,102,116,126,130,132,135^ four of these studies were among exclusively Hispanic^100,141^ or exclusive or predominantly Latina^79,140^ mothers, one study was among exclusively Chinese mothers,^111^ one study was among 65 percent Black, 15 percent Asian or Asian American, 15 percent Other, and 5 percent White mothers,^81^ one study was among half African American and half African-born mothers,^88^ one study included half African American and half Puerto Rican mothers,^107^ and one study was among 65 percent Hispanic mothers, and smaller racial and ethnic groups including White and other mothers.^124^ Among the 10 studies reporting negative breastfeeding themes,^78,82,91,96,99,106,108,114,116,129^ mothers indicated a lack of support from their partner, including negative comments, social stigma, and opposition to breastfeeding. Nine of these studies were exclusively or predominantly among African American mothers,^78,82,91,99,106,108,114,116,129^ and one study included a diverse sample including Puerto Rican, West Indian/Jamaican, African American, other ethnic/racial, and White mothers.^96^

Social support from family was an overarching theme in 42 studies (44 articles)^74,77,79,80,82,83,88–91,95,96,98–102,105–107,109,111–117,119–121,124,126,129,130,132,135,136,138–143^ with 30 studies (32 articles) reporting on positive breastfeeding themes^74,80,82,83,88,90,91,95,96,98,99,101,102,105,107,112,114–117,119,120,126,130,132,135,138–143^ and 24 studies reporting on negative breastfeeding themes.^74,77,79,88,89,100,105–107,109,111,113–116,121,124,126,129,136,138–140,143^ Among the 30 studies (32 articles) reporting positive breastfeeding themes,^74,80,82,83,88,90,91,95,96,98,99,101,102,105,107,112,114–117,119,120,126,130,132,135,138–143^ mothers indicated receiving support from their mothers and other relatives through encouragement, advice and information, and having family role models. Sixteen of these studies (18 articles) were among exclusively or predominantly African American mothers,^74,82,83,91,95,99,101,102,114,116,119,120,126,130,132,135,142,143^ 5 of these studies were among exclusively or predominantly Hispanic^80,105,117,141^ or Latina^117,140^ mothers, and one study each was conducted among exclusively Somali,^98^ Korean,^112^ and Brazilian^115^ mothers. The remaining studies included one study among half African American and half African-born mothers,^88^ one study among 60 percent White and 40 percent African American mothers,^90^ one study with a diverse sample including Puerto Rican, West Indian/Jamaican, African American, other ethnic/racial, and White mothers,^96^ one study among half African American and half Puerto Rican mothers,^107^ one study among 55 percent Somali and 45 percent Mexican mothers,^138^ and one study among 45 percent African American and 34 percent White mothers and smaller racial and ethnic groups including Hispanic and other mothers.^139^ Among the 24 studies reporting negative breastfeeding themes,^74,77,79,88,89,100,105–107,109,111,113–116,121,124,126,129,136,138–140,143^ mothers mentioned that there was a lack of support from family members, including negative comments, misinformation and worries from older generations, and a lack of hands-on or in-person support. Eleven of these studies were among exclusive or predominantly African American mothers,^74,89,106,109,113,114,116,121,126,129,143^ four were among exclusively Hispanic^100,105^ or exclusively or predominantly Latina^79,140^ mothers, and one study each was conducted exclusively among Somali,^136^ Chinese,^111^ and Brazilian^115^ mothers. Among the remaining studies, one was among half Burundian and half Congolese mothers,^77^ one was among half African American and half African-born mothers,^88^ one included half African American and half Puerto Rican mothers,^107^ one was among 65 percent Hispanic mothers, and smaller racial and ethnic groups including White and other mothers,^124^ one was among 55 percent Somali and 45 percent Mexican mothers,^138^ and one included 45 percent African American and 34 percent White mothers and smaller racial and ethnic groups including Hispanic and other mothers.^139^

Social support from social network was an overarching theme in 36 studies (37 articles)^74,78–83,88,90,91,99,101,102,106–109,112–118,120,121,124,126,127,129,130,132,133,135,136,139,141^ with 22 studies (23 articles) reporting positive breastfeeding themes^74,80,82,83,88,90,91,99,101,102,107,108,112,114,116–118,127,130,132,133,135,141^ and 25 studies reporting negative breastfeeding themes.^74,78,79,81,82,90,99,101,106,107,109,113–115,118,120,121,124,126,129,130,132,135,136,139^ Among the 22 studies (23 articles) reporting positive breastfeeding themes,^74,80,82,83,88,90,91,99,101,102,107,108,112,114,116–118,127,130,132,133,135,141^ mothers indicated receiving social support from friends, social media, and other members of their community (e.g., church), such as through advice or information, stories, and encouragement. Fifteen of these articles were among exclusively or predominantly African American mothers,^74,82,83,91,99,101,102,108,114,116,127,130,132,133,135^ four were among exclusive or predominantly Hispanic^80,117,118,141^ or Latina^117^ one study was among exclusively Korean mothers,^112^ one study was among half African American and half African-born mothers,^88^ one study was among 60 percent White and 40 percent African American mothers,^90^ and one study included half African American and half Puerto Rican mothers.^107^ Among the 25 studies reporting negative breastfeeding themes,^74,78,79,81,82,90,99,101,106,107,109,113–115,118,120,121,124,126,129,130,132,135,136,139^ mothers indicated feeling judgment about and opposition to breastfeeding from their social network, discouragement from friends, and a lack of discussion or encouragement from friends. Sixteen of these studies were among exclusively or predominantly African American mothers,^74,78,82,99,101,106,109,113,114,120,121,126,129,130,132,135^ two were among predominantly Hispanic^118^ or predominantly Latina^79^ mothers, one study each was among exclusively Somali^136^ and Brazilian^115^ mothers, one study was among 65 percent Black, 15 percent Asian or Asian American, 15 percent Other, and 5 percent White mothers,^81^ one study was among 60 percent White and 40 percent African American mothers,^90^ one study included half African American and half Puerto Rican mothers,^107^ one study was among 65 percent Hispanic mothers, and smaller racial and ethnic groups including White and other mothers,^124^ and one study included 45 percent African American and 34 percent White mothers and smaller racial ethnic groups including Hispanic and other mothers.^139^

##### NIMHD framework: interpersonal level – health care system domain

Within the interpersonal level and health care system domain, one qualitative factor was examined: information and support from health care providers.^74,75,78–81,84–86,88–91,95,96,98,99,101–105,107–109,112–116,118,119,121,125,126,128,130,132–139,141^

Information and support from health care providers was an overarching theme in 44 studies (46 articles),^74,75,78–81,84–86,88–91,95,96,98,99,101–105,107–109,112–116,118,119,121,125,126,128,130,132–139,141^ with 36 studies (37 articles) reporting positive breastfeeding themes,^74,78–81,84,86,88,90,95,96,98,99,101,102,105,107,108,112,113,115,116,118,119,125,126,128,130,132–139,141^ and 30 (31 articles) reporting negative breastfeeding themes.^74,75,78,79,84,85,88,89,91,95,96,99,101,103,104,107,109,113,114,116,118,119,121,125,128,130,132,135,136,138,139^ Among the 36 studies (37 articles) that reported positive breastfeeding themes,^74,78–81,84,86,88,90,95,96,98,99,101,102,105,107,108,112,113,115,116,118,119,125,126,128,130,132–139,141^ mothers indicated that they received breastfeeding information, practical breastfeeding assistance, and breastfeeding encouragement or promotion from health care providers, and that they trusted this advice and information from health care providers. Eighteen of these studies were among exclusively or predominantly African American mothers,^74,78,84,86,95,99,101,102,108,113,116,119,126,128,130,132,133,135^ six studies were among exclusively or predominantly Hispanic^80,105,118,141^ or Latina^79,134^ mothers, two studies were among exclusively Somali mothers,^98,136^ and one study each was among exclusively Korean^112^ and Brazilian^115^ mothers. Among the remaining studies, one study was among 65 percent Black, 15 percent Asian or Asian American, 15 percent Other, and 5 percent White mothers,^81^ one study was among half African American and half African-born mothers,^88^ one study was among 60 percent White and 40 percent African American mothers,^90^ one study included a diverse sample including Puerto Rican, West Indian/Jamaican, African American, other ethnic/racial, and White mothers,^96^ one study included half African American and half Puerto Rican mothers,^107^ one study was among 60 percent Latina mothers, and smaller racial and ethnic groups including Black, Asian, and White mothers,^125^ one study was among 54 percent Hispanic, 31 percent Black, and smaller racial and ethnic groups including Asian, bi-/multiracial/other and White mothers,^137^ one study was among 55 percent Somali and 45 percent Mexican mothers,^138^ and one study included 45 percent African American and 34 percent White mothers and smaller racial and ethnic groups including Hispanic and other mothers.^139^ Among the 30 studies (31 articles) reporting on negative breastfeeding themes,^74,75,78,79,84,85,88,89,91,95,96,99,101,103,104,107,109,113,114,116,118,119,121,125,128,130,132,135,136,138,139^ mothers indicated a lack of support from their health care provider, such as health care providers not encouraging breastfeeding, health care providers that are indifferent or discouraging, a lack of discussion about breastfeeding with health care providers, and stigma or discrimination by health care providers. Twenty-one of these articles were among exclusively African American mothers,^74,78,84,85,89,91,95,99,101,103,104,109,113,114,116,119,121,128,130,132,135^ two studies were among predominantly Hispanic^118^ and predominantly Latina^79^ mothers, one study was among exclusively Somali mothers,^136^ one study included 56 percent African American and 44 percent Caucasian mothers,^75^ one study was among half African American and half African-born mothers,^88^ one study included a diverse sample including Puerto Rican, West Indian/Jamaican, African American, other ethnic/racial, and White mothers,^96^ one study included half African American and half Puerto Rican mothers,^107^ one study was among 60 percent Latina mothers, and smaller racial and ethnic groups including Black, Asian, and White mothers,^125^ one study was among 55 percent Somali and 45 percent Mexican mothers,^138^ and one study included 45 percent African American and 34 percent White mothers and smaller racial and ethnic groups including Hispanic and other mothers.^139^

##### NIMHD framework: community level – physical/ built environment domain

Within the community level and physical/built environment domain, one qualitative factor was examined: community resources and support,^73,74,77,78,80,81,83–86,88–91,95,96,99,101–103,105,107–109,112,113,115–121,123,129,132,134,135,139,140^ which was subdivided into breastfeeding resources^73,74,77,78,80,81,84–86,88–91,95,99,101,102,107,108,112,113,116–119,121,132,134,135,139,140^ and community social support.^73,74,78,80,81,83,85,86,95,96,99,101,103,105,107–109,115,116,120,121,123,129,132,135,139^

Community resources and support was an overarching theme in 40 articles^73,74,77,78,80,81,83–86,88–91,95,96,99,101–103,105,107–109,112,113,115–121,123,129,132,134,135,139,140^ that was subdivided into two categories: breastfeeding resources^73,74,77,78,80,81,84–86,88–91,95,99,101,102,107,108,112,113,116–119,121,132,134,135,139,140^ and community social support.^73,74,78,80,81,83,85,86,95,96,99,101,103,105,107–109,115,116,120,121,123,129,132,135,139^

Breastfeeding resources was an overarching theme in 29 studies (31 articles),^73,74,77,78,80,81,84–86,88–91,95,99,101,102,107,108,112,113,116–119,121,132,134,135,139,140^ with 16 studies (17 articles) reporting positive breastfeeding themes^73,74,80,84,89,90,95,99,101,107,108,112,116,118,119,135,139^ and 19 studies reporting negative breastfeeding themes.^73,77,78,81,85,86,88,90,91,102,107,113,116,117,119,121,132,134,140^ Among the 16 studies (17 articles) reporting positive breastfeeding themes,^73,74,80,84,89,90,95,99,101,107,108,112,116,118,119,135,139^ mothers indicated receiving breastfeeding information from the internet (including social media), magazines and books, and classes. Mothers specifically mentioned WIC as a source of breastfeeding information, from classes or prenatal workshops, and pumps in several studies.^84,99,101,107,139^ Among the 17 articles with positive breastfeeding themes, 11 were among exclusively African American mothers,^73,74,84,89,95,99,101,108,116,119,135^ 2 were among predominantly Hispanic mothers,^80,118^ 1 study was among exclusively Korean mothers,^112^ 1 study was among 60 percent White and 40 percent African American mothers,^90^ 1 study included half African American and half Puerto Rican mothers,^107^ and 1 study included 45 percent African American and 34 percent White mothers and smaller racial and ethnic groups including Hispanic and other mothers.^139^ Among the 19 studies reporting negative breastfeeding themes,^73,77,78,81,85,86,88,90,91,102,107,113,116,117,119,121,132,134,140^ mothers frequently indicated receiving free formula from WIC,^77,78,85,102,107,121,132,134^ or the government,^140^ which made it easy to stop breastfeeding; additionally, mothers mentioned a lack of access to breastfeeding education due to a lack of transportation, materials in Spanish, and awareness of breastfeeding resources including pumps. Among the 19 studies reporting negative breastfeeding themes, 11 were among exclusively African American mothers,^73,78,85,86,91,102,113,116,119,121,132^ 3 were among exclusively Hispanic^117^ or Latina^117,134,140^ mothers, 1 study was among half Burundian and half Congolese mothers,^77^ 1 study was among 65 percent Black, 15 percent Asian or Asian American, 15 percent Other, and 5 percent White mothers,^81^ 1 study was among half African American and half African-born mothers,^88^ 1 study was among 60 percent White and 40 percent African American mothers,^90^ and 1 study included half African American and half Puerto Rican mothers.^107^

Community social support was an overarching theme in 25 studies (26 articles)^73,74,78,80,81,83,85,86,95,96,99,101,103,105,107–109,115,116,120,121,123,129,132,135,139^ with 19 studies (20 articles) reporting on positive breastfeeding themes^73,74,78,80,81,83,85,86,95,96,101,105,107,115,116,120,121,129,135,139^ and 8 studies (9 articles) reporting on negative breastfeeding themes.^73,74,78,99,103,108,109,123,132^. Among the 19 studies (20 articles) reporting on positive breastfeeding themes,^73,74,78,80,81,83,85,86,95,96,101,105,107,115,116,120,121,129,135,139^ mothers indicated positive social support from social media, peer counselors, WIC representatives, and other breastfeeding mothers in their community, such as members of their church. Thirteen of these articles were among exclusively or predominantly African American mothers,^73,74,78,83,85,86,95,101,116,120,121,129,135^ two were among exclusively or predominantly Hispanic mothers,^80,105^ one study was among exclusively Brazilian mothers,^115^ one study was among 65 percent Black, 15 percent Asian or Asian American, 15 percent Other, and 5 percent White mothers,^81^ one study was among a diverse sample including Puerto Rican, West Indian/Jamaican, African American, other ethnic/racial, and White mothers,^96^ one study was among half African American and half Puerto Rican mothers,^107^ one study was among 45 percent African American and 34 percent White mothers and smaller racial and ethnic groups including Hispanic and other mothers.^139^ Among the eight studies reporting on negative breastfeeding themes,^73,74,78,99,103,108,109,123,132^ mothers indicated a lack of social support from their community, including and social media. Mothers specifically indicated a lack of social support from WIC peer counselors in three studies.^78,99,132^ All of these studies were among exclusively African American mothers.^73,74,78,99,103,108,109,123,132^

##### NIMHD framework: community level – sociocultural environment domain

Within the community level and sociocultural environment domain, one qualitative theme was examined: cultural beliefs, practices, and norms.^76,77,88,99,100,107,108,111–113,115–117,135,136,138,140,141^

Cultural beliefs, practices, and norms was an overarching theme in 18 studies,^76,77,88,99,100,107,108,111–113,115–117,135,136,138,140,141^ with 11 studies reporting positive breastfeeding themes^77,88,99,100,107,112,113,115,135,138,141^ and 12 studies reporting negative breastfeeding themes.^76,88,108,111,112,115–117,136,138,140,141^ Among the 11 studies reporting positive breastfeeding themes,^77,88,99,100,107,112,113,115,135,138,141^ mothers primarily indicated that breastfeeding is normal in their culture, while mothers in some studies mentioned that breastfeeding is what God intended. Among the 11 studies with positive breastfeeding themes,^77,88,99,100,107,112,113,115,135,138,141^ 3 were among exclusively African American mothers,^99,113,135^ 2 were among exclusively Hispanic mothers,^100,141^ 1 study each was among exclusively Korean^112^ and Brazilian^115^ mothers, 1 study was among half African American and half African-born mothers,^88^ 1 study included half African American and half Puerto Rican mothers,^107^ and 1 study was among 55 percent Somali and 45 percent Mexican mothers.^138^ Among the 12 studies reporting negative breastfeeding themes,^76,88,108,111,112,115–117,136,138,140,141^ mothers indicated sentiments such as that the breastfeeding culture in the United States is unsupportive, that their cultural practices related to breastfeeding were different than those of the United State more broadly, and that information and advice from their culture differed from that provided in the United States. Some examples of different information and cultural practices included cultural belief to discard first milk,^138,140^ timing of introduction of solid foods,^115^ introducing traditionally Chinese solid foods early,^111^ spending the first 40 days at home exclusively breastfeeding,^136^ and the cultural belief to rest.^138^ Among the 12 studies with negative breastfeeding themes,^76,88,108,111,112,115–117,136,138,140,141^ 2 were among exclusively African American mothers,^108,116^ 3 were among exclusively Hispanic^117,141^ or Latina^117,140^ mothers, 1 study each was among exclusively Somali,^136^ Marshallese,^76^ Chinese,^111^ Korean,^112^ and Brazilian^115^ mothers, 1 study was among half African American and half African-born mothers,^88^ and 1 study was among 55 percent Somali and 45 percent Mexican mothers.^138^

##### NIMHD framework: community level – health care system domain

Within the community level and health care system domain, two qualitative factors were examined: hospital practices^79,84,85,95,107,128,134,137^ and lack of support after discharge.^84,91,128,132^

Hospital practices was a theme in eight studies,^79,84,85,95,107,128,134,137^ with one study reporting a positive breastfeeding theme,^85^ and eight studies reporting negative breastfeeding themes.^79,84,85,95,107,128,134,137^ The one positive breastfeeding theme pertained to rooming-in policies at hospitals in a study among exclusively African American mothers.^85^ Among the eight studies reporting negative breastfeeding themes,^79,84,85,95,107,128,134,137^ mothers primarily indicated that formula was given to them or their infant without consent or when the mother requested not to provide formula, despite mothers wanting to breastfeed, while one study highlighted the lack of supportive hospital practices more generally. Half of these studies were among exclusively African American mothers,^84,85,95,128^ two were among exclusively or predominantly Latina mothers,^79,134^ one study included half African American and half Puerto Rican mothers,^107^ and one study was among 54 percent Hispanic, 31 percent Black, and smaller racial and ethnic groups including Asian, bi-/multiracial/other and White mothers.^137^

Lack of support after hospital discharge was an overarching theme in four studies,^84,91,128,132^ all of which were negative. Mothers indicated that they had difficulty getting support or were reluctant to get support after being discharged from the hospital.^84,91,128,132^ All of these studies were among exclusively African American mothers.

##### NIMHD framework: societal level – behavioral domain

Within the societal level and behavioral domain, one qualitative factor was examined: maternity leave and breastfeeding laws.^85,86,115^

Maternity leave and breastfeeding laws was an overarching theme in three studies,^85,86,115^ with one study reporting a positive breastfeeding theme^85^ and two studies reporting negative breastfeeding themes.^86,115^ The one positive breastfeeding theme related to paid maternity leave and workplace protections for nursing mothers among exclusively African American mothers.^85^ The two negative breastfeeding themes related to a lack of paid parental leave and a lack of maternity leave in the United States.^86,115^ One study was among exclusively African American mothers,^86^ and one study was among exclusively Brazilian mothers.^115^

##### NIMHD framework: societal level – sociocultural environment domain

Within the societal level and sociocultural environment domain, two qualitative factors were examined: breastfeeding in public^74,76–78,82,83,85,90,91,95,99,100,102,104,107–109,114–117,121–123,130,132,135,136,138,140^ and historical context.^85,87,99,116,143^

Breastfeeding in public was an overarching theme in 30 studies,^74,76–78,82,83,85,90,91,95,99,100,102,104,107–109,114–117,121–123,130,132,135,136,138,140^ with 5 studies reporting positive breastfeeding themes^78,83,107,123,135^ and 30 studies reporting negative breastfeeding themes.^74,76–78,82,83,85,90,91,95,99,100,102,104,107–109,114–117,121–123,130,132,135,136,138,140^ Among the five studies reporting positive breastfeeding themes,^78,83,107,123,135^ participants mentioned feeling comfortable with breastfeeding in public, that having a cover increased comfort when breastfeeding in public, and that there were places that were supportive of breastfeeding in public. Four of these studies were among exclusively or predominantly African American mothers,^78,83,123,135^ and one study included half African American and half Puerto Rican mothers.^107^ Among the 30 studies reporting negative breastfeeding themes,^74,76–78,82,83,85,90,91,95,99,100,102,104,107–109,114–117,121–123,130,132,135,136,138,140^ mothers mentioned that breastfeeding in public was challenging due to stigma and feelings of embarrassment and discomfort, as well as a lack of convenient or supportive places to breastfeed in public. Twenty of these studies were among exclusively or predominantly African American mothers,^74,78,82,83,85,91,95,99,102,104,108,109,114,116,121–123,130,132,135^ three studies were among exclusively Hispanic^100,117^ or Latina^117,140^ mothers, one study was among exclusively Somali mothers,^136^ one study was among exclusively Marshallese mothers,^76^ one study was among exclusively Brazilian mothers,^115^ one study was among half Burundian and half Congolese mothers,^77^ one study was among 60 percent White and 40 percent African American mothers,^90^ one study included half African American and half Puerto Rican mothers,^107^ and one study was among 55 percent Somali and 45 percent Mexican mothers.^138^

Historical context was an overarching theme in five studies,^85,87,99,116,143^ with one study reporting a positive breastfeeding theme^143^ and four studies reporting negative breastfeeding themes.^85,87,99,116^ The one study which reported a positive breastfeeding theme indicated a pro-breastfeeding perspective to frame the historical context of breastfeeding and was conducted exclusively among African American women.^143^ Among the negative breastfeeding themes,^85,87,99,116^ participants mentioned the negative historical context of slavery and the exploitation of Black women as wet nurses. All of these studies were among exclusively African American mothers.