# Chapter 2 What are the racial and/or ethnic disparities in human milk feeding in the United States? (Key Question 1)

## Plain-language summary

#### What is the question?

What are the racial and/or ethnic disparities in human milk feeding in the United States?

#### Why was this question asked?

To summarize evidence on racial and ethnic disparities in human milk feeding in order to inform Food and Nutrition Service (FNS) communication and program guidance on this topic.

#### How was this question answered?

The Nutrition Evidence Systematic Review (NESR) team summarized analyses from the Centers for Disease Control and Prevention’s (CDC’s) National Immunization Survey-Child (NIS-Child) and the U.S. Department of Agriculture (USDA) FNS’ Special Supplemental Nutrition Program for Women, Infants, and Children (WIC) Participant and Program Characteristics 2020 final report to answer these questions.

#### What was the population of interest?

The population of interest is parent-infant dyads living in the United States.

#### How up-to-date are these data?

The summary included data from the CDC’s NIS-Child for children born in the years 2012 through 2019 and data from the WIC Participant and Program Characteristics 2020 final report (collected in April 2020).

#### What evidence was found and what is the answer to the question?

- [underlined: CDC NIS-Child]: Data from the CDC’s NIS-Child for children born in the years 2012 through 2019 were reviewed. The following outcomes were available: ever breastfed, any breastfeeding at 6 months, any breastfeeding at 12 months, exclusive breastfeeding at 3 months, and exclusive breastfeeding at 6 months. Non-Hispanic Black children had the lowest rates of ever breastfeeding, any breastfeeding at 6 and 12 months, and exclusive breastfeeding at 3 and 6 months. Results for children of other races and/or ethnicities varied, but Non-Hispanic Asian and Non-Hispanic White children tended to have the highest rates of these outcomes.
- [underlined: WIC Participant and Program Characteristics 2020]: Data from the WIC Participant and Program Characteristics 2020 final report were reviewed. All data was collected in April 2020. The following outcomes were available: ever or currently breastfed, breastfeeding at 3 months, breastfeeding at 6 months, and breastfeeding at 12 months. The data was summarized by race and ethnicity separately. When data was summarized by race, Black infants and children had the lowest rates of ever or currently breastfed and breastfeeding at 3, 6, or 12 months. When data was summarized by ethnicity, Hispanic/Latino infants and children had the highest rates of these outcomes.

## Abstract

#### Background

Racial and ethnic disparities in human milk feeding practices are present in the United States.^a^,^b^,^c^ To inform communication and program guidance on these topics, the Nutrition Evidence Systematic Review (NESR), housed in the Center for Nutrition Policy and Promotion (CNPP), Food and Nutrition Service (FNS), U.S. Department of Agriculture (USDA), conducted a rapid review project for the Office of Policy Support (OPS), FNS, USDA.

a Li R, Perrine CG, Anstey EH, Chen J, MacGowan CA, Elam-Evans LD. Breastfeeding trends by race/ethnicity among US children born from 2009 to 2015. JAMA Pediatr. 2019;173(12):e193319. doi:10.1001/jamapediatrics.2019.3319 31609438

b Chiang KV, Li R, Anstey EH, Perrine CG. Racial and ethnic disparities in breastfeeding initiation – United States, 2019. MMWR Morb Mortal Wkly Rep. 2021;70(21):769–774. doi:10.15585/mmwr.mm7021a1 34043611

c Jones KM, Power ML, Queenan JT, Schulkin J. Racial and ethnic disparities in breastfeeding. Breastfeed Med. 2015;10(4):186–196. doi:10.1089/bfm.2014.0152 25831234

One of the objectives of this project was to answer the following question: What are the racial and/or ethnic disparities in human milk feeding in the United States?

#### Methods

NESR analysts accessed summarized data on human milk feeding outcomes from the Centers for Disease Control and Prevention’s (CDC) National Immunization Survey-Child (NIS-Child), collected in children born in the years 2012 through 2019,^d^ and the USDA FNS’ Special Supplemental Nutrition Program for Women, Infants, and Children (WIC) Participant and Program Characteristics 2020 final report, collected in infants and children participating in WIC in April 2020.^e^ NESR analysts then described and qualitatively assessed the summarized data on human milk feeding outcomes between racial and/or ethnic groups and, for the NIS-Child data, over time.

d Centers for Disease Control and Prevention. Results: Breastfeeding Rates, National Immunization Surveys (NIS). Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/results.html

e Kline N, Zvavitch P, Wroblewska K, Worden M, Mwombela B, Thorn B. WIC Participant and Program Characteristics 2020. U.S. Department of Agriculture, Food and Nutrition Service. 2022. Accessed November 8, 2022. https://www.fns.usda.gov/wic/participant-program-characteristics-2020

#### Results

Based on data from the CDC’s NIS-Child and the USDA FNS’ WIC Participant and Program Characteristics 2020 final report, racial and/or ethnic disparities are apparent in human milk feeding initiation, human milk feeding duration, and exclusive human milk feeding duration – a trend that has persisted across the past approximately 10 years. In both datasets, the lowest rates of human milk feeding initiation and human milk feeding at 6 and 12 months were consistently observed for Black or Non-Hispanic Black. the lowest rates of exclusive human milk feeding at 3 and 6 months were also observed among Non-Hispanic Black individuals (outcomes which were only examined in NIS-Child). In data from the WIC Participant and Program Characteristics 2020 final report, individuals of Hispanic/Latino ethnicity had higher rates of human milk feeding initiation and human milk feeding at 3, 6, and 12 months relative to individuals who were not of Hispanic/Latino ethnicity. (Race and ethnicity were not examined separately in the summarized data from the CDC’s NIS-Child.) Although data from NIS-Child and the WIC Participant and Program Characteristics 2020 final report are not directly comparable (e.g., different methods to collect data, different categorizations of race and/or ethnicity), across racial and/or ethnic groups human milk feeding initiation and duration appeared to be lower among WIC participants (assessed in the WIC Participant and Program Characteristics 2020 final report) compared to the general population (assessed in NIS-Child). Because statistical comparisons were not made between racial and/or ethnic groups, or across time, trends in the data should be interpreted with caution.

## Results

The methods used to answer the Key Question 1, What are the racial and/or ethnic disparities in human milk feeding in the U.S.?, are described in Chapter 1.

### CDC NIS-Child, 2012-2019

The CDC’s NIS-Child^a^ provides data that suggests racial and ethnic disparities in human milk feeding outcomes that are persistent among children born in the years 2012 through 2019. There were relatively small sample sizes and lack of summarized data for later birth years for Non-Hispanic American Indian/Alaska Native and Non-Hispanic Hawaiian/Pacific Islander children. Therefore, the description of the data focused on Hispanic, Non-Hispanic Asian, Non-Hispanic Black, and Non-Hispanic White children, and children of two or more races (i.e., groups with summarized data for each available birth year).

a Centers for Disease Control and Prevention. Results: Breastfeeding Rates, National Immunization Surveys (NIS). Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/results.html

#### Ever breastfed

Summarized data from the CDC’s NIS-Child on infants and children ever breastfed is presented in Table 7 and Figure 2. Trends for the racial and/or ethnic groups with summarized data for each available birth year (2012-2019) are summarized below.

Among Hispanic, Non-Hispanic Asian, Non-Hispanic Black, and Non-Hispanic White children, and children of two or more races born in 2012, the group with the lowest percentage of children who were ever breastfed was Non-Hispanic Black children (66.4 percent). In contrast, the groups with the highest percentage of children who were ever breastfed were Non-Hispanic Asian (83.2 percent), Non-Hispanic White (83.0 percent), and Hispanic (82.4 percent) children. Among children of two or more races, 75.4 percent were ever breastfed.

The rates of ever breastfeeding within each racial and ethnic group fluctuated over the 8 birth years, with a trend towards rising rates among all racial and ethnic groups from 2012 to 2019. Among children born in 2019, the group with the lowest percentage of children who were ever breastfed was still Non-Hispanic Black children (74.1 percent), although this was 7.7 percentage points higher than in 2012. In contrast, the group with the highest percentage of children who were ever breastfed was Non-Hispanic Asian (90.8 percent, 7.6 percentage points higher than in 2012), followed by Non-Hispanic White (85.3 percent, 2.3 percentage points higher than in 2012) and Hispanic (83.0 percent, 0.6 percentage points higher than in 2012) children, and children of two or more races (82.7 percent, 7.3 percentage points higher than in 2012).

#### Any breastfeeding at 6 and 12 months

Summarized data from the CDC’s NIS-Child on children breastfed for 6 and 12 months are presented in Table 8, Table 9, Figure 3, and Figure 4. Trends for the racial and/or ethnic groups with summarized data for each available birth year (2012-2019) are summarized below.

Among Hispanic, Non-Hispanic Asian, Non-Hispanic Black, and Non-Hispanic White children, and children of two or more races born in 2012, the group with the lowest percentage of children who were breastfed for 6 months (35.3 percent) and 12 months (16.9 percent) was Non-Hispanic Black children. In contrast, the group with highest percentage of children who were breastfed at 6 months (65.6 percent) and 12 months (42.3 percent) was Non-Hispanic Asian children, followed by Non-Hispanic White children (6 months: 55.8 percent, 12 months: 32.8 percent), Hispanic children (6 months: 51.4 percent, 12 months: 27.9 percent), and children of two or more races (6 months: 46.2 percent, 12 months: 25.3 percent).

The rates of any breastfeeding fluctuated over the 8 birth years. Among children born in 2019, the group with the lowest percentage of children who were breastfed for 6 months (44.0 percent) and 12 months (24.1 percent) was still Non-Hispanic Black children; however, these were 8.7 and 7.2 percentage points higher, respectively, than for Non-Hispanic Black children born in 2012. The group with the highest percentage of children breastfed at 6 months (70.2 percent, 4.6 percentage points higher than in 2012) and 12 months (45.7 percent, 3.4 percentage points higher than in 2012) was Non-Hispanic Asian children. Children of other races and/or ethnicities were intermediate, including Non-Hispanic White children (6 months: 59.9 percent, 4.1 percentage points higher than in 2012; 12 months: 39.4 percent, 6.6 percentage points higher than in 2012), children of two or more races (6 months: 57.1 percent, 10.9 percentage points higher than in 2012; 12 months: 38.1 percent, 12.8 percentage points higher than in 2012), and Hispanic children (6 months: 51.4 percent, 0 percentage point difference from 2012; 12 months: 33.2 percent, 5.3 percentage points higher than in 2012).

#### Exclusive breastfeeding at 3 and 6 months

Summarized data from the CDC’s NIS-Child on children exclusively breastfeeding at 3 and 6 months are presented in Table 10, Table 11, Figure 5, and Figure 6. Trends for the racial and/or ethnic groups with summarized data for each available birth year (2012-2019) are summarized below.

Among Hispanic, Non-Hispanic Asian, Non-Hispanic Black, and Non-Hispanic White children, and children of two or more races born in 2012, the group with the lowest percentage of children who were exclusively breastfeeding through 3 months (33.4 percent) and 6 months (13.9 percent) was Non-Hispanic Black children. In contrast, the groups with the highest percentage of children who were exclusively breastfeeding through 3 and 6 months were Non-Hispanic White (3 months: 48.0 percent, 6 months: 24.4 percent) and Non-Hispanic Asian (3 months: 46.5 percent, 6 months: 26.9 percent) children, followed by children of two or more races (3 months: 41.4 percent, 6 months: 23.0 percent) and Hispanic children (3 months: 40.3 percent, 6 months: 20.8 percent).

Rates of exclusive breastfeeding fluctuated over the 8 birth years. Among children born in 2019, the group with the lowest percentage of children who were exclusively breastfeeding through 3 months (36.3 percent) and 6 months (19.1 percent) was still Non-Hispanic Black children; these were 2.9 and 5.2 percentage points higher, respectively, than Non-Hispanic Black children who were born in 2012. The group with the highest percentage of children who were exclusively breastfeeding through 3 months (49.0 percent, 1.0 percentage point higher than in 2012) was Non-Hispanic White children, followed by children of two or more races (47.4 percent, 6.0 percentage points higher than in 2012), Hispanic children (43.8 percent, 3.5 percentage points higher than in 2012), and Non-Hispanic Asian children (42.5 percent, 4.0 percentage points lower than in 2012). The group with the highest percentage of children who were exclusively breastfeeding through 6 months (28.5 percent, 1.6 percentage points higher than in 2012) was Non-Hispanic Asian children, followed by children of two or more races (27.0 percent, 4.0 percentage points higher than in 2012), Non-Hispanic White children (26.9 percent, 2.5 percentage points higher than in 2012), and Hispanic children (23.5 percent, 2.7 percentage points higher than in 2012).

Table 7 Rates of ever breastfeeding by birth year and race and ethnicity from NIS-Child^*^,^†^

Race and Ethnicity | Measure | 2012 | 2013 | 2014 | 2015 | 2016 | 2017 | 2018 | 2019
Hispanic | % ± half 95% CI | 82.4±2.8 | 83.0±2.4 | 84.8±2.4 | 84.6±2.4 | 82.9±3.0 | 84.1±2.4 | 85.0±1.9 | 83.0±2.3
Hispanic | n | 2,788 | 3,425 | 3,275 | 3,723 | 4,030 | 4,376 | 4,336 | 3,991
Non-Hispanic American Indian/Alaska Native | % ± half 95% CI | 71.5±12.6 | 68.3±9.9 | 79.5±7.1 | 76.4±11.3 | NR | 80.7±8.5 | NA | NA
Non-Hispanic American Indian/Alaska Native | n | 217 | 242 | 259 | 265 | NR | 257 | 279 | 295
Non-Hispanic Asian | % ± half 95% CI | 83.2±7.6 | 83.8±4.8 | 80.7±7.3 | 89.3±3.5 | 88.2±3.4 | 90.0±3.3 | 92.4±2.4 | 90.8±2.9
Non-Hispanic Asian | n | 683 | 727 | 796 | 796 | 685 | 855 | 951 | 1,119
Non-Hispanic Black | % ± half 95% CI | 66.4±3.8 | 66.3±3.6 | 68.0±3.5 | 69.4±3.5 | 74.0±3.6 | 73.7±3.5 | 75.5±3.0 | 74.1±3.7
Non-Hispanic Black | n | 1,476 | 1,662 | 1,666 | 1,607 | 1,587 | 1,851 | 1,996 | 2,144
Non-Hispanic Hawaiian/Pacific Islander | % ± half 95% CI | 83.9±14.1 | 75.0±12.4 | 79.9±13.2 | 83.0±13.8 | NR | 85.2±9.6 | NA | NA
Non-Hispanic Hawaiian/Pacific Islander | n | 96 | 92 | 117 | 95 | NR | 105 | 113 | 113
Non-Hispanic White | % ± half 95% CI | 83.0±1.3 | 84.3±1.2 | 85.7±1.1 | 85.9±1.2 | 86.6±1.2 | 86.7±1.2 | 85.3±1.2 | 85.3±1.3
Non-Hispanic White | n | 8,811 | 9,135 | 9,742 | 9,907 | 9,667 | 11,112 | 12,032 | 11,465
Two or More Races | % ± half 95% CI | 75.4±6.5 | 79.0±4.5 | 79.9±3.6 | 82.5±3.8 | 84.2±3.4 | 83.7±3.3 | 82.4±3.3 | 82.7±3.4
Two or More Races | n | 1,070 | 1,158 | 1,254 | 1,280 | 1,304 | 1,460 | 1,721 | 1,779

* Abbreviations: %, percent; ±, plus or minus; CI, confidence interval

† Data presented in Table 7 were extracted from:

Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2012. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/rates-any-exclusive-bf-socio-dem-2012.htm

Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2013. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/rates-any-exclusive-bf-socio-dem-2013.htm

Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2014. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/rates-any-exclusive-bf-socio-dem-2014.htm

Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2015. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/rates-any-exclusive-bf-socio-dem-2015.htm

Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2016. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/rates-any-exclusive-bf-socio-dem-2016.htm

Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2017. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/rates-any-exclusive-bf-socio-dem-2017.html

Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2018. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/rates-any-exclusive-bf-socio-dem-2018.html

Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2019. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/data-files/2019/rates-any-exclusive-bf-socio-dem-2019.html

Figure 2 Rates of ever breastfeeding by birth year and race and ethnicity from NIS-Child^*^ * Abbreviations: %, percent; ±, plus or minus; CI, confidence interval ^†^ † Data presented in Figure 2 (also presented in Table 7) were extracted from: Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2012. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/rates-any-exclusive-bf-socio-dem-2012.htm Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2013. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/rates-any-exclusive-bf-socio-dem-2013.htm Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2014. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/rates-any-exclusive-bf-socio-dem-2014.htm Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2015. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/rates-any-exclusive-bf-socio-dem-2015.htm Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2016. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/rates-any-exclusive-bf-socio-dem-2016.htm Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2017. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/rates-any-exclusive-bf-socio-dem-2017.html Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2018. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/rates-any-exclusive-bf-socio-dem-2018.html Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2019. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/data-files/2019/rates-any-exclusive-bf-socio-dem-2019.html

This figure illustrates the rates of ever breastfeeding by birth year and race/ethnicity from NIS-Child for infants who are Hispanic, Non-Hispanic Asian, Non-Hispanic Black, Non-Hispanic White, or Two or More Races. This data is presented in table format in Table 7.

Table 8 Rates of any breastfeeding at 6 months by birth year and race and ethnicity from NIS-Child^*^,^†^

Race and Ethnicity | Measure | 2012 | 2013 | 2014 | 2015 | 2016 | 2017 | 2018 | 2019
Hispanic | % ± half 95% CI | 51.4±3.7 | 45.6±3.5 | 52.5±3.5 | 54.1±3.3 | 51.6±3.9 | 55.4±3.3 | 52.8±2.8 | 51.4±2.9
Hispanic | n | 2,788 | 3,425 | 3,275 | 3,723 | 4,030 | 4,376 | 4,336 | 3,991
Non-Hispanic American Indian/Alaska Native | % ± half 95% CI | 28.8±11.7 | 41.3±9.5 | 52.8±10.1 | 55.0±12.4 | NR | NA | NA | NA
Non-Hispanic American Indian/Alaska Native | n | 217 | 242 | 259 | 265 | NR | 257 | 279 | 295
Non-Hispanic Asian | % ± half 95% CI | 65.6±7.7 | 64.4±5.9 | 61.9±7.1 | 72.2±5.2 | 72.1±5.7 | 73.5±5.0 | 75.6±4.2 | 70.2±4.9
Non-Hispanic Asian | n | 683 | 727 | 796 | 796 | 685 | 855 | 951 | 1,119
Non-Hispanic Black | % ± half 95% CI | 35.3±4.0 | 39.1±3.7 | 41.5±3.7 | 44.7±3.8 | 48.6±3.8 | 47.8±3.7 | 49.3±3.5 | 44.0±3.7
Non-Hispanic Black | n | 1,476 | 1,662 | 1,666 | 1,607 | 1,587 | 1,851 | 1,996 | 2,144
Non-Hispanic Hawaiian/Pacific Islander | % ± half 95% CI | 32.6±19.0 | 50.2±13.8 | 68.1±13.5 | 57.8±16.3 | NR | NA | NA | NA
Non-Hispanic Hawaiian/Pacific Islander | n | 96 | 92 | 117 | 95 | NR | 105 | 113 | 113
Non-Hispanic White | % ± half 95% CI | 55.8±1.8 | 57.9±1.7 | 60.0±1.6 | 62.0±1.6 | 61.5±1.8 | 61.9±1.7 | 60.0±1.5 | 59.9±1.7
Non-Hispanic White | n | 8,811 | 9,135 | 9,742 | 9,907 | 9,667 | 11,112 | 12,032 | 11,465
Two or More Races | % ± half 95% CI | 46.2±6.2 | 51.0±5.6 | 53.4±4.8 | 55.5±5.0 | 58.0±5.3 | 56.5±5.5 | 52.9±4.0 | 57.1±4.3
Two or More Races | n | 1,070 | 1,158 | 1,254 | 1,280 | 1,304 | 1,460 | 1,721 | 1,779

* Abbreviations: %, percent; ±, plus or minus; CI, confidence interval

† Data presented in Table 8 were extracted from:

Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2012. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/rates-any-exclusive-bf-socio-dem-2012.htm

Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2013. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/rates-any-exclusive-bf-socio-dem-2013.htm

Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2014. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/rates-any-exclusive-bf-socio-dem-2014.htm

Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2015. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/rates-any-exclusive-bf-socio-dem-2015.htm

Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2016. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/rates-any-exclusive-bf-socio-dem-2016.htm

Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2017. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/rates-any-exclusive-bf-socio-dem-2017.html

Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2018. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/rates-any-exclusive-bf-socio-dem-2018.html

Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2019. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/data-files/2019/rates-any-exclusive-bf-socio-dem-2019.html

Figure 3 Rates of any breastfeeding at 6 months by birth year and race and ethnicity from NIS-Child^*^ * Abbreviations: %, percent; ±, plus or minus; CI, confidence interval ^†^ † Data presented in Figure 3 (also presented in Table 8) were extracted from: Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2012. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/rates-any-exclusive-bf-socio-dem-2012.htm Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2013. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/rates-any-exclusive-bf-socio-dem-2013.htm Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2014. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/rates-any-exclusive-bf-socio-dem-2014.htm Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2015. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/rates-any-exclusive-bf-socio-dem-2015.htm Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2016. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/rates-any-exclusive-bf-socio-dem-2016.htm Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2017. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/rates-any-exclusive-bf-socio-dem-2017.html Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2018. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/rates-any-exclusive-bf-socio-dem-2018.html Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2019. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/data-files/2019/rates-any-exclusive-bf-socio-dem-2019.html

This figure illustrates the rates of any breastfeeding at 6 months by birth year and race/ethnicity from NIS-Child for infants who are Hispanic, Non-Hispanic Asian, Non-Hispanic Black, Non-Hispanic White, or Two or More Races. This data is presented in table format in Table 8.

Table 9 Rates of any breastfeeding at 12 months by birth year and race and ethnicity from NIS-Child^*^,^†^

Race and Ethnicity | Measure | 2012 | 2013 | 2014 | 2015 | 2016 | 2017 | 2018 | 2019
Hispanic | % ± half 95% CI | 27.9±3.6 | 25.7±2.9 | 31.7±3.4 | 32.6±3.1 | 32.1±3.6 | 33.9±3.3 | 32.3±2.6 | 33.2±2.7
Hispanic | n | 2,788 | 3,425 | 3,275 | 3,723 | 4,030 | 4,376 | 4,336 | 3,991
Non-Hispanic American Indian/Alaska Native | % ± half 95% CI | 17.9±8.9 | 21.6±7.4 | 29.7±9.8 | 31.3±10.7 | NR | NA | NA | NA
Non-Hispanic American Indian/Alaska Native | n | 217 | 242 | 259 | 265 | NR | 257 | 279 | 295
Non-Hispanic Asian | % ± half 95% CI | 42.3±7.0 | 38.7±5.8 | 37.5±6.3 | 50.3±6.8 | 51.6±7.2 | 50.0±6.7 | 51.2±4.9 | 45.7±5.1
Non-Hispanic Asian | n | 683 | 727 | 796 | 796 | 685 | 855 | 951 | 1,119
Non-Hispanic Black | % ± half 95% CI | 16.9±3.1 | 19.3±2.8 | 21.5±3.1 | 24.0±3.2 | 27.1±3.4 | 26.1±3.3 | 27.9±3.2 | 24.1±2.8
Non-Hispanic Black | n | 1,476 | 1,662 | 1,666 | 1,607 | 1,587 | 1,851 | 1,996 | 2,144
Non-Hispanic Hawaiian/Pacific Islander | % ± half 95% CI | 14.4±9.0 | 32.6±13.3 | 31.7±12.3 | 24.4±11.7 | NR | NA | NA | NA
Non-Hispanic Hawaiian/Pacific Islander | n | 96 | 92 | 117 | 95 | NR | 105 | 113 | 113
Non-Hispanic White | % ± half 95% CI | 32.8±1.8 | 36.1±1.6 | 37.8±1.6 | 39.8±1.6 | 39.6±1.8 | 38.2±1.7 | 37.6±1.5 | 39.4±1.6
Non-Hispanic White | n | 8,811 | 9,135 | 9,742 | 9,907 | 9,667 | 11,112 | 12,032 | 11,465
Two or More Races | % ± half 95% CI | 25.3±5.4 | 30.2±5.5 | 32.8±4.9 | 35.9±5.0 | 38.5±5.6 | 31.0±5.4 | 32.8±3.5 | 38.1±4.2
Two or More Races | n | 1,070 | 1,158 | 1,254 | 1,280 | 1,304 | 1,460 | 1,721 | 1,779

* Abbreviations: %, percent; ±, plus or minus; CI, confidence interval

† Data presented in Table 9 were extracted from:

Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2012. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/rates-any-exclusive-bf-socio-dem-2012.htm

Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2013. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/rates-any-exclusive-bf-socio-dem-2013.htm

Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2014. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/rates-any-exclusive-bf-socio-dem-2014.htm

Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2015. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/rates-any-exclusive-bf-socio-dem-2015.htm

Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2016. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/rates-any-exclusive-bf-socio-dem-2016.htm

Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2017. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/rates-any-exclusive-bf-socio-dem-2017.html

Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2018. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/rates-any-exclusive-bf-socio-dem-2018.html

Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2019. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/data-files/2019/rates-any-exclusive-bf-socio-dem-2019.html

Figure 4 Rates of any breastfeeding at 12 months by birth year and race and ethnicity from NIS-Child^*^ * Abbreviations: %, percent; ±, plus or minus; CI, confidence interval ^†^ † Data presented in Figure 4 (also presented in Table 9) were extracted from: Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2012. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/rates-any-exclusive-bf-socio-dem-2012.htm Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2013. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/rates-any-exclusive-bf-socio-dem-2013.htm Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2014. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/rates-any-exclusive-bf-socio-dem-2014.htm Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2015. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/rates-any-exclusive-bf-socio-dem-2015.htm Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2016. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/rates-any-exclusive-bf-socio-dem-2016.htm Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2017. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/rates-any-exclusive-bf-socio-dem-2017.html Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2018. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/rates-any-exclusive-bf-socio-dem-2018.html Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2019. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/data-files/2019/rates-any-exclusive-bf-socio-dem-2019.html

This figure illustrates the rates of any breastfeeding at 12 mo by birth year and race/ethnicity from NIS-Child for infants who are Hispanic, Non-Hispanic Asian, Non-Hispanic Black, Non-Hispanic White, or Two or More Races. This data is presented in table format in Table 9.

Table 10 Rates of exclusive breastfeeding through 3 months by birth year and race and ethnicity from NIS-Child^*^,^†^

Race and Ethnicity | Measure | 2012 | 2013 | 2014 | 2015 | 2016 | 2017 | 2018 | 2019
Hispanic | % ± half 95% CI | 40.3±3.8 | 40.4±3.5 | 45.5±3.6 | 42.2±3.3 | 42.0±3.9 | 41.5±3.3 | 42.6±2.8 | 43.8±2.9
Hispanic | n | 2,749 | 3,355 | 3,197 | 3,636 | 3,954 | 4,282 | 4,222 | 3,903
Non-Hispanic American Indian/Alaska Native | % ± half 95% CI | 27.4±11.8 | 33.1±9.2 | 51.2±10.2 | 44.6±12.1 | NR | NA | NA | NA
Non-Hispanic American Indian/Alaska Native | n | 212 | 233 | 252 | 257 | NR | 252 | 268 | 291
Non-Hispanic Asian | % ± half 95% CI | 46.5±7.5 | 41.6±6.0 | 44.3±7.0 | 45.7±7.0 | 48.1±7.6 | 47.7±6.9 | 50.0±5.1 | 42.5±5.1
Non-Hispanic Asian | n | 662 | 706 | 757 | 767 | 655 | 811 | 914 | 1,076
Non-Hispanic Black | % ± half 95% CI | 33.4±4.1 | 28.9±3.3 | 32.7±3.5 | 36.0±3.8 | 39.1±3.7 | 38.7±3.7 | 39.3±3.5 | 36.3±3.5
Non-Hispanic Black | n | 1,460 | 1,630 | 1,620 | 1,573 | 1,555 | 1,805 | 1,955 | 2,075
Non-Hispanic Hawaiian/Pacific Islander | % ± half 95% CI | 43.3±24.1 | 36.3±13.3 | 59.5±14.7 | 45.3±16.6 | NR | NA | NA | NA
Non-Hispanic Hawaiian/Pacific Islander | n | 95 | 87 | 114 | 89 | NR | 100 | 112 | 112
Non-Hispanic White | % ± half 95% CI | 48.0±1.9 | 51.6±1.7 | 51.5±1.7 | 53.0±1.7 | 52.9±1.9 | 52.4±1.8 | 50.6±1.6 | 49.0±1.7
Non-Hispanic White | n | 8,546 | 8,815 | 9,375 | 9,537 | 9,310 | 10,765 | 11,616 | 11,060
Two or More Races | % ± half 95% CI | 41.4±6.3 | 44.2±5.8 | 42.5±4.9 | 46.5±5.1 | 46.6±5.5 | 43.9±5.8 | 44.5±3.9 | 47.4±4.3
Two or More Races | n | 1,044 | 1,135 | 1,207 | 1,243 | 1,260 | 1,402 | 1,673 | 1,700

* Abbreviations: %, percent; ±, plus or minus; CI, confidence interval

† Data presented in Table 10 were extracted from:

Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2012. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/rates-any-exclusive-bf-socio-dem-2012.htm

Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2013. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/rates-any-exclusive-bf-socio-dem-2013.htm

Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2014. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/rates-any-exclusive-bf-socio-dem-2014.htm

Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2015. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/rates-any-exclusive-bf-socio-dem-2015.htm

Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2016. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/rates-any-exclusive-bf-socio-dem-2016.htm

Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2017. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/rates-any-exclusive-bf-socio-dem-2017.html

Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2018. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/rates-any-exclusive-bf-socio-dem-2018.html

Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2019. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/data-files/2019/rates-any-exclusive-bf-socio-dem-2019.html

Figure 5 Rates of exclusive breastfeeding through 3 months by birth year and race and ethnicity from NIS-Child^*^ * Abbreviations: %, percent; ±, plus or minus; CI, confidence interval ^†^ † Data presented in Figure 5 (also presented in Table 10) were extracted from: Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2012. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/rates-any-exclusive-bf-socio-dem-2012.htm Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2013. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/rates-any-exclusive-bf-socio-dem-2013.htm Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2014. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/rates-any-exclusive-bf-socio-dem-2014.htm Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2015. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/rates-any-exclusive-bf-socio-dem-2015.htm Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2016. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/rates-any-exclusive-bf-socio-dem-2016.htm Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2017. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/rates-any-exclusive-bf-socio-dem-2017.html Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2018. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/rates-any-exclusive-bf-socio-dem-2018.html Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2019. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/data-files/2019/rates-any-exclusive-bf-socio-dem-2019.html

This figure illustrates the rates of exclusive breastfeeding through 3 months by birth year and race/ethnicity from NIS-Child for infants who are Hispanic, Non-Hispanic Asian, Non-Hispanic Black, Non-Hispanic White, or Two or More Races. This data is presented in table format in Table 10.

Table 11 Rates of exclusive breastfeeding through 6 months by birth year and race and ethnicity from NIS-Child^*^,^†^

Race and Ethnicity | Measure | 2012 | 2013 | 2014 | 2015 | 2016 | 2017 | 2018 | 2019
Hispanic | % ± half 95% CI | 20.8±3.3 | 19.1±2.7 | 24.5±3.4 | 20.9±2.6 | 20.4±2.9 | 21.5±2.7 | 23.3±2.3 | 23.5±2.5
Hispanic | n | 2,749 | 3,355 | 3,197 | 3,636 | 3,954 | 4,282 | 4,222 | 3,903
Non-Hispanic American Indian/Alaska Native | % ± half 95% CI | 12.5±6.5 | 17.9±7.0 | 26.5±10.2 | 19.6±7.2 | NR | NA | NA | NA
Non-Hispanic American Indian/Alaska Native | n | 212 | 233 | 252 | 257 | NR | 252 | 268 | 291
Non-Hispanic Asian | % ± half 95% CI | 26.9±7.1 | 20.9±4.6 | 27.6±6.4 | 30.1±5.8 | 31.8±7.9 | 26.8±6.7 | 33.3±4.8 | 28.5±4.5
Non-Hispanic Asian | n | 662 | 706 | 757 | 767 | 655 | 811 | 914 | 1,076
Non-Hispanic Black | % ± half 95% CI | 13.9±2.9 | 14.6±2.7 | 15.0±2.7 | 17.2±3.1 | 20.7±3.2 | 21.2±3.4 | 19.8±2.8 | 19.1±2.8
Non-Hispanic Black | n | 1,460 | 1,630 | 1,620 | 1,573 | 1,555 | 1,805 | 1,955 | 2,075
Non-Hispanic Hawaiian/Pacific Islander | % ± half 95% CI | 11.8±9.5 | 20.0±10.1 | 29.9±12.0 | 29.0±15.1 | NR | NA | NA | NA
Non-Hispanic Hawaiian/Pacific Islander | n | 95 | 87 | 114 | 89 | NR | 100 | 112 | 112
Non-Hispanic White | % ± half 95% CI | 24.4±1.7 | 26.8±1.5 | 27.9±1.5 | 29.5±1.6 | 29.1±1.7 | 28.7±1.5 | 28.8±1.4 | 26.9±1.5
Non-Hispanic White | n | 8,546 | 8,815 | 9,375 | 9,537 | 9,310 | 10,765 | 11,616 | 11,060
Two or More Races | % ± half 95% CI | 23.0±5.6 | 19.8±3.8 | 21.2±4.7 | 21.9±3.8 | 24.1±4.2 | 26.6±6.0 | 23.7±3.3 | 27.0±3.8
Two or More Races | n | 1,044 | 1,135 | 1,207 | 1,243 | 1,260 | 1,402 | 1,673 | 1,700

* Abbreviations: %, percent; ±, plus or minus; CI, confidence interval

† Data presented in Table 11 were extracted from:

Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2012. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/rates-any-exclusive-bf-socio-dem-2012.htm

Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2013. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/rates-any-exclusive-bf-socio-dem-2013.htm

Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2014. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/rates-any-exclusive-bf-socio-dem-2014.htm

Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2015. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/rates-any-exclusive-bf-socio-dem-2015.htm

Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2016. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/rates-any-exclusive-bf-socio-dem-2016.htm

Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2017. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/rates-any-exclusive-bf-socio-dem-2017.html

Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2018. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/rates-any-exclusive-bf-socio-dem-2018.html

Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2019. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/data-files/2019/rates-any-exclusive-bf-socio-dem-2019.html

Figure 6 Rates of exclusive breastfeeding through 6 months by birth year and race and ethnicity from NIS-Child^*^ * Abbreviations: %, percent; ±, plus or minus; CI, confidence interval ^†^ † Data presented in Figure 6 (also presented in Table 11) were extracted from: Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2012. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/rates-any-exclusive-bf-socio-dem-2012.htm Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2013. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/rates-any-exclusive-bf-socio-dem-2013.htm Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2014. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/rates-any-exclusive-bf-socio-dem-2014.htm Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2015. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/rates-any-exclusive-bf-socio-dem-2015.htm Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2016. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/rates-any-exclusive-bf-socio-dem-2016.htm Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2017. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/rates-any-exclusive-bf-socio-dem-2017.html Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2018. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/rates-any-exclusive-bf-socio-dem-2018.html Centers for Disease Control and Prevention. Rates of Any and Exclusive Breastfeeding by Socio-demographics among Children Born in 2019. Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/data-files/2019/rates-any-exclusive-bf-socio-dem-2019.html

This figure illustrates the rates of exclusive breastfeeding through 6 months by birth year and race/ethnicity from NIS-Child for infants who are Hispanic, Non-Hispanic Asian, Non-Hispanic Black, Non-Hispanic White, or Two or More Races. This data is presented in table format in Table 11.

### WIC Participant and Program Characteristics 2020

The USDA FNS’ WIC Participant and Program Characteristics 2020 final report provides data collected in April 2020 that suggests racial and ethnic disparities in human milk feeding outcomes among infants and children participating in WIC. Summarized data from the WIC Participant and Program Characteristics 2020 final report are presented in Table 12.

#### Ever or currently breastfed

Breastfeeding initiation was highest among Pacific Islander infants and children (79.3 percent), followed by Asian (77.8 percent) and American Indian (76.5 percent) infants and children. Breastfeeding initiation was lowest among Black infants and children (64.2 percent); infants and children who were White (73.6 percent), of two or more races (72.3 percent), or did not have a reported race (73.0 percent) were intermediate. In regard to ethnicity, breastfeeding initiation was higher among Hispanic/Latino infants and children (78.0 percent) compared to infants and children who were Non-Hispanic/Latino (68.0 percent) or did not have a reported ethnicity (39.7 percent).

#### Breastfeeding at 3 months

Breastfeeding at 3 months was highest among Asian infants and children (43.9 percent), followed by infants and children who did not have a reported race (43.1 percent), who were Pacific Islander (40.8 percent), and who were American Indian (40.2 percent). Breastfeeding at 3 months was lowest among Black infants and children (27.0 percent), followed by infants and children who were White (33.3 percent) or were of two or more races (32.0 percent). In regard to ethnicity, breastfeeding at 3 months was higher among Hispanic/Latino infants and children (37.4 percent) compared to infants and children who were Non-Hispanic/Latino (30.0 percent) or did not have a reported ethnicity (20.8 percent).

#### Breastfeeding at 6 months

Breastfeeding at 6 months was highest among infants and children without a race (33.6 percent), followed by Asian (31.4 percent), American Indian (30.1 percent), and Pacific Islander (26.2 percent) infants and children. Breastfeeding at 6 months was lowest among Black infants and children (16.9 percent), followed by infants and children were of two or more races (21.6 percent) or were White (22.6 percent). In regard to ethnicity, breastfeeding at 6 months was higher among Hispanic/Latino infants and children (26.2 percent) compared to infants and children who were Non-Hispanic/Latino (19.8 percent) or did not have a reported ethnicity (13.3 percent).

#### Breastfeeding at 12 months

Breastfeeding at 12 months was highest among Asian children (19.1 percent), followed by American Indian (17.4 percent), White (16.2 percent), and Pacific Islander (15.8 percent) children. Breastfeeding at 12 months was lowest among Black children (10.8 percent), followed by children of two or more races (12.2 percent) and children who did not have a reported race (12.9 percent). In regard to ethnicity, breastfeeding at 12 months was higher among Hispanic/Latino children (18.6 percent) compared to children who were Non-Hispanic/Latino (12.4 percent) or did not have a reported ethnicity (8.9 percent).

Table 12 Human milk feeding initiation and duration by race and ethnicity among WIC participants, April 2020^*^,^†^

Race or Ethnicity | Measure | Ever or Currently Breastfed^‡^ | Breastfeeding at 3 mo^§^ | Breastfeeding at 6 mo^§^ | Breastfeeding at 12 mo^**^
American Indian | % | 76.5 | 40.2 | 30.1 | 17.4
American Indian | n (total) | 60,075 | 33,620 | 33,620 | 11,820
Asian | % | 77.8 | 43.9 | 31.4 | 19.1
Asian | n (total) | 32,349 | 18,958 | 18,958 | 7,380
Black | % | 64.2 | 27.0 | 16.9 | 10.8
Black | n (total) | 217,435 | 124,378 | 124,378 | 47,080
Pacific Islander | % | 79.3 | 40.8 | 26.2 | 15.8
Pacific Islander | n (total) | 8,066 | 4,513 | 4,513 | 1,578
White | % | 73.6 | 33.3 | 22.6 | 16.2
White | n (total) | 504,866 | 290,929 | 290,929 | 121,649
Two or More Races | % | 72.3 | 32.0 | 21.6 | 12.2
Two or More Races | n (total) | 69,833 | 40,859 | 40,859 | 15,084
Race Not Reported | % | 73.0 | 43.1 | 33.6 | 12.9
Race Not Reported | n (total) | 6,214 | 3,593 | 3,593 | 2,635
Hispanic/Latino | % | 78.0 | 37.4 | 26.2 | 18.6
Hispanic/Latino | n (total) | 326,772 | 185,276 | 185,276 | 80,751
Non-Hispanic/Latino | % | 68.0 | 30.0 | 19.8 | 12.4
Non-Hispanic/Latino | n (total) | 571,182 | 331,055 | 331,055 | 126,351
Ethnicity Not Reported | % | 39.7 | 20.8 | 13.3 | 8.9
Ethnicity Not Reported | n (total) | 885 | 520 | 520 | 124

* Abbreviations: %, percentage; mo, months

† Data extracted from Kline N, Zvavitch P, Wroblewska K, Worden M, Mwombela B, Thorn B. Chapter 8. Breastfeeding Initiation and Duration. WIC Participant and Program Characteristics 2020. U.S. Department of Agriculture, Food and Nutrition Service. 2022. Accessed November 8, 2022. https://www.fns.usda.gov/wic/participant-program-characteristics-2020

‡ Assessed in 6-13-month-old infants and children

§ Assessed in 9-13-month-old infants and children

** Assessed in 12-13-month-old children

## Summary of data

Based on data from the CDC’s NIS-Child and the USDA FNS’ WIC Participant and Program Characteristics 2020 final report, racial and/or ethnic disparities are apparent in human milk feeding initiation, human milk feeding duration, and exclusive human milk feeding duration – a trend that has persisted across the past approximately 10 years. In both datasets, the lowest rates of human milk feeding initiation and human milk feeding at 6 and 12 months were consistently observed for Black or Non-Hispanic Black. the lowest rates of exclusive human milk feeding at 3 and 6 months were also observed among Non-Hispanic Black individuals (outcomes which were only examined in NIS-Child). In data from the WIC Participant and Program Characteristics 2020 final report, individuals of Hispanic/Latino ethnicity had higher rates of human milk feeding initiation and human milk feeding at 3, 6, and 12 months relative to individuals who were not of Hispanic/Latino ethnicity. (Race and ethnicity were not examined separately in the summarized data from the CDC’s NIS-Child.) Although data from NIS-Child and the WIC Participant and Program Characteristics 2020 final report are not directly comparable (e.g., different methods to collect data, different categorizations of race and/or ethnicity), across racial and/or ethnic groups human milk feeding initiation and duration appeared to be lower among WIC participants (assessed in the WIC Participant and Program Characteristics 2020 final report) compared to the general population (assessed in NIS-Child). Because statistical comparisons were not made between racial and/or ethnic groups, or across time, trends in the data should be interpreted with caution.