# Chapter 1 Introduction and project methods

## Introduction

Studies have identified racial and ethnic disparities in infant feeding practices in the United States.^a,b,c^ The purpose of this project was to summarize evidence on racial and ethnic disparities in human milk feeding, as well as evidence on factors associated with these disparities, including, but not limited to, economic hardship, poverty, food insecurity, access to care and support, education, family structure, acculturation, and beliefs and perceptions. Additionally, interventions, programs, initiatives, and policies that aim to address racial and ethnic disparities in human milk feeding were reviewed. The objective of this project was to answer the following questions.

a Li R, Perrine CG, Anstey EH, Chen J, MacGowan CA, Elam-Evans LD. Breastfeeding trends by race/ethnicity among US children born from 2009 to 2015. JAMA Pediatr. 2019;173(12):e193319. doi:10.1001/jamapediatrics.2019.3319 31609438

b Chiang KV, Li R, Anstey EH, Perrine CG. Racial and ethnic disparities in breastfeeding initiation – United States, 2019. MMWR Morb Mortal Wkly Rep. 2021;70(21):769–774. doi:10.15585/mmwr.mm7021a1 34043611

c Jones KM, Power ML, Queenan JT, Schulkin J. Racial and ethnic disparities in breastfeeding. Breastfeed Med. 2015;10(4):186–196. doi:10.1089/bfm.2014.0152 25831234

- Key Question 1:
  What are the racial and/or ethnic disparities in human milk feeding in the United States?
- Key Question 2:
  What factors are associated with racial and/or ethnic disparities in human milk feeding in the United States?
- Key Question 3:
  What interventions, programs, initiatives, and policies impact racial and/or ethnic disparities in human milk feeding in the United States, and do impacts vary across different racial and/or ethnic, socioeconomic, and geographic groups?

A team from the Nutrition Evidence Systematic Review (NESR)^d^ at the Center for Nutrition Policy and Promotion (CNPP), Food and Nutrition Service (FNS), U.S. Department of Agriculture (USDA) summarized existing data and conducted rapid reviews to answer these questions. NESR specializes in conducting food- and nutrition-related reviews using rigorous, protocol-driven methodology. This project was initiated and funded by the Office of Policy Support (OPS), FNS, USDA. A summary of previous milestones for this project are provided in Table 1.

d A list of abbreviations used throughout the text of this report is presented in Appendix 1.

Table 1 Project milestones

Date | Description | Citation or URL
July 14, 2022 | Protocol registration submitted | https://www.crd.york.ac.uk/prospero
July 25, 2022 | Protocol registration posted | https://www.crd.york.ac.uk/prospero/display_record.php?RecordID=346575

## Project methods

NESR used different methods to answer Key Question 1 and Key Questions 2 and 3.

- NESR answered Key Question 1 by describing existing, summarized data from the Centers for Disease Control and Prevention’s (CDC) National Immunization Survey-Child (NIS-Child),^a^ and for Special Supplemental Nutrition Program for Women, Infants, and Children (WIC) participants, data from the USDA FNS’ WIC Participant and Program Characteristics 2020 final report.^b^
  a Centers for Disease Control and Prevention. Results: Breastfeeding Rates, National Immunization Surveys (NIS). Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/results.html
  b Kline N, Zvavitch P, Wroblewska K, Worden M, Mwombela B, Thorn B. WIC Participant and Program Characteristics 2020. U.S. Department of Agriculture, Food and Nutrition Service. 2022. Accessed November 8, 2022. https://www.fns.usda.gov/wic/participant-program-characteristics-2020
- NESR answered Key Question 2 and Key Question 3 by conducting rapid reviews. A NESR rapid review is an evidence synthesis project that answers a nutrition question of public health importance using streamlined systematic review methods.

A detailed description of the methods that NESR analysts and the NESR librarian used during this project follows.

### Develop a project analytic framework

Figure 1 is the project analytic framework. It depicts the variables of interest and the associations or relationships between them, which the project examined. Consistent with recommendations from the Academy of Breastfeeding Medicine,^c^ gender-inclusive language has been used to describe human milk feeding and the parent-infant dyad, when appropriate.^d^ Additionally, the phrases “race and/or ethnicity” and “race and ethnicity” are used throughout the report, when appropriate, which acknowledges that race and ethnicity are two different constructs.^e^

c Bartick M, Stehel EK, Calhoun SL, Feldman-Winter L, Zimmerman D, Noble L, Rosen-Carole C, Kair LR, Academy of Breastfeeding Medicine. Academy of breastfeeding medicine position statement and guideline: infant feeding and lactation-related language and gender. Breastfeed Med. 2021;16(8),587–590. doi: 10.1089/bfm.2021.29188.abm 34314606

d Studies on human milk feeding vary in the terminology used to characterize infant feeding and precision in which the gender identity and sex of study participants are described. NESR used inclusive language, when possible and appropriate, to describe human milk feeding and individuals who lactate, especially in circumstances in which specific information on gender and biological sex are not available. Further, when the use of gender-neutral language was not appropriate, NESR used terminology for gender (e.g., woman, man) rather than biological sex (e.g., female, male). Terminology used by individual studies to describe human milk feeding and individuals who lactate was reported in data extraction tables, the description of the evidence, and the evidence synthesis for clarity and accuracy. Regardless of the terminology used in individual studies, the term “human milk feeding” was used in summary statements.

e Individual studies may analyze race and ethnicity as separate variables or may analyze race and ethnicity as a single combined variable. Terminology consistent with the data source, in terms of the overarching variable to describe race and/or ethnicity as well as how individual racial and/or ethnic groups were described, was reported in data extraction tables, the description of the evidence, and the evidence synthesis for accuracy.

Figure 1 Project analytic framework^a^ a Abbreviations: KQ1, Key Question 1; KQ2, Key Question 2; KQ3, Key Question 3

[underlined: Key Questions]:

1. What are the racial and/or ethnic disparities in human milk feeding in the United States?
2. What factors are associated with racial and/or ethnic disparities in human milk feeding in the United States?
3. What interventions, programs, initiatives, and policies impact racial and/or ethnic disparities in human milk feeding in the United States, and do impacts vary across different racial and/or ethnic, socioeconomic, and geographic groups?

Box A [underlined: Race and/or ethnicity] – Typically, Box A would depict an intervention given to, or exposure observed in, the target population. However, this project used the term “independent variable” because race and/or ethnicity is neither an intervention nor an exposure. We examined race and/or ethnicity in parent-infant dyads living in the United States.
Box B [underlined: Human milk feeding] – The outcomes (dependent variables) of interest are human milk feeding initiation, human milk feeding duration, and exclusive human milk feeding duration. In addition to these outcomes, Key Question 2 and Key Question 3 considered disparities in meeting human milk feeding intentions.
Box C [underlined: Factors] – Key Question 2 identified factors associated with racial and/or ethnic disparities in human milk feeding. For quantitative studies, factors were mediators (i.e., factors that lie on the path between race and/or ethnicity and human milk feeding disparities) and moderators (i.e., factors that change the strength of the association between race and/or ethnicity and human milk feeding disparities). For qualitative studies, factors that are associated with the relationship between race and/or ethnicity and human milk feeding outcomes were identified.
Box D [underlined: Interventions, programs, initiatives, and policies] – Key Question 3 identified studies that assess the impact of interventions, programs, initiatives, and policies that aim to improve human milk feeding rates in racially and ethnically diverse populations.

### Use existing data to answer Key Question 1

The following describes the methods used to answer Key Question 1. The question, “What are the racial and/or ethnic disparities in human milk feeding in the United States” was answered using CDC’s nationally-representative, publicly available data. Additionally, national data from WIC participants were also summarized to identify any similarities or differences from CDC’s nationally-representative data. Existing, summarized data from federal sources were assessed, in lieu of conducting a rapid review, because it was believed that these data would be the most generalizable to the U.S. population, including low-income mothers who participate in WIC, and provide a comprehensive approach to answer this question. The results for Key Question 1 are presented in Chapter 2.

#### Access relevant data

NESR analysts accessed summarized data from the CDC’s NIS-Child^a^ to describe racial and/or ethnic disparities in human milk feeding in the United States. The survey^b^ asked respondents, who were parents and guardians of 19- to 35-month-old children, questions about race and/or ethnicity and human milk feeding practices. The CDC summarized data by child year of birth; summarized data were available for birth years 2012 through 2019.

a Centers for Disease Control and Prevention. Results: Breastfeeding Rates, National Immunization Surveys (NIS). Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/results.html

b Centers for Disease Control and Prevention. NIS-Child Data and Documentation for 2015 to Present. Accessed December 27, 2022. https://www.cdc.gov/vaccines/imz-managers/nis/datasets.html

The CDC’s NIS-Child asked the following survey questions about race and ethnicity:

a. Is [child’s name] of Hispanic or Latino origin?
b. Please choose one or more of the following categories to describe [child’s name] race. Is [child’s name] White, Black or African American, American Indian, Alaska Native, Asian, Native Hawaiian or other Pacific Islander?

The CDC codes the responses from the two questions above into a single race and ethnicity variable with the following categories:

- Hispanic
- Non-Hispanic White
- Non-Hispanic Black
- Non-Hispanic Asian
- Non-Hispanic Hawaiian/Pacific Islander
- Non-Hispanic American Indian/Alaska Native
- Two or More Races

The following survey questions about human milk feeding were used by the CDC NIS-Child:

a. Was [child] ever breastfed or fed breastmilk?
b. How old was [child’s name] when [child’s name] completely stopped breastfeeding or being fed breast milk?
c. How old was [child’s name] when [he/she] was first fed formula?
d. This next question is about the first thing that [child] was given other than breast milk or formula. Please include juice, cow’s milk, sugar water, baby food, or anything else that [child] may have been given, even water. How old was [child’s name] when (he/she) was first fed anything other than breast milk or formula?

NESR analysts then accessed summarized data from the USDA FNS’ WIC Participant and Program Characteristics 2020 final report^a^ to describe racial and/or ethnic disparities in human milk feeding in the United States among WIC participants. Summarized data based on the following variables from the Minimum Data Set (data elements that State WIC agencies are required to submit to FNS) collected in April 2020 were accessed:

a. Race and Ethnicity: Individuals were classified based on ethnicity (Hispanic/Latino, Non-Hispanic/Latino) and race (American Indian or Alaska Native, Asian, Black or African American, Native Hawaiian or Other Pacific Islander, White). Multiple categories of race could be selected for an individual.
b. Currently Breastfed: For infants and children aged 6 through 13 months in April 2020, whether the participant was being breastfed at that time.
c. Ever Breastfed: For infants and children aged 6 through 13 months in April 2020, whether the participant ever received breastmilk.
d. Length of Time Breastfed: For infants and children aged 6 through 13 months in April 2020, the number of weeks the participant received breastmilk.

a Kline N, Zvavitch P, Wroblewska K, Worden M, Mwombela B, Thorn B. WIC Participant and Program Characteristics 2020. U.S. Department of Agriculture, Food and Nutrition Service. 2022. Accessed November 8, 2022. https://www.fns.usda.gov/wic/participant-program-characteristics-2020

#### Extract data

One NESR analyst extracted summarized data from the CDC NIS-Child^a^ and the USDA FNS’ WIC Participant and Program Characteristics 2020 final report,^a^ which included the human milk feeding outcomes, sample sizes, and results by birth year (CDC NIS-Child only) and by race and/or ethnicity. A second NESR analyst reviewed the extracted results for completeness, accuracy, and consistent presentation and formatting. Any disagreements were reconciled between analysts. Evidence tables and graphs were created by NESR analysts using the extracted data.

#### Describe the data

NESR analysts described the CDC-summarized NIS-Child data^b^ for children with birth years of 2012 through 2019 to qualitatively summarize human milk feeding outcomes between racial and/or ethnic groups and across time. There were relatively small sample sizes and lack of summarized data for later birth years for Non-Hispanic American Indian/Alaska Native and Non-Hispanic Hawaiian/Pacific Islander children. Therefore, the description of the data focused on Hispanic, Non-Hispanic Asian, Non-Hispanic Black, and Non-Hispanic White children, and children of two or more races (i.e., groups with summarized data for each available birth year). The human milk feeding outcomes summarized by the CDC included: ever breastfed, breastfed at 6 months, breastfed at 12 months, exclusive breastfeeding through 3 months, and exclusive breastfeeding through 6 months. No statistical analyses comparing different racial and/or ethnic groups or comparing different survey years by human milk feeding outcomes were conducted by NESR.

b Centers for Disease Control and Prevention. Results: Breastfeeding Rates, National Immunization Surveys (NIS). Accessed November 8, 2022. https://www.cdc.gov/breastfeeding/data/nis_data/results.html

NESR analysts described summarized data from the USDA FNS’ WIC Participant and Program Characteristics 2020 final report^a^ to qualitatively summarize human milk feeding outcomes between racial and/or ethnic groups among WIC participants in April 2020. The human milk feeding outcomes summarized in the report included: ever or currently breastfed (breastfeeding initiation) among infants and children 6-13 months old, breastfeeding at 3 and 6 months among infants and children 9-13 months old, and breastfeeding at 12 months among children 12-13 months old. No statistical analyses comparing different racial and/or ethnic groups by human milk feeding outcomes were conducted by NESR.

a Shea BJ, Reeves BC, Wells G, . AMSTAR 2: a critical appraisal tool for systematic reviews that include randomised or non-randomised studies of healthcare interventions, or both. BMJ. 2017;358:j4008. Published 2017 Sep 21. doi:10.1136/bmj.j4008 28935701

### Conduct rapid reviews to answer Key Questions 2 and 3

The following describes the methods used to answer Key Question 2 and Key Question 3. The results for Key Question 2 are presented in Chapter 3 and the results for Key Question 3 are presented in Chapter 4.

#### Develop a protocol

A rapid review protocol is the plan for how NESR’s methodology will be used to conduct a specific rapid review and is established by NESR, a priori, before any evidence is reviewed. The protocol is designed to capture the most appropriate and relevant body of evidence to answer the rapid review question. Development of the protocol involves discussion of the strengths and limitations of various methodological approaches relevant to the question, which then inform subsequent steps of the systematic review process. The protocol describes all of the methods that will be used throughout the rapid review process. Additionally, the protocol includes the following components, which are tailored to each rapid review question: the analytic framework, inclusion and exclusion criteria, and synthesis plan.

Prior to finalizing the rapid review protocols for Key Question 2 and Key Question 3, NESR analysts and the NESR librarian conducted an informal search for relevant, existing rapid and systematic reviews. NESR may use existing non-NESR reviews to answer a rapid or systematic review question if they are: 1) relevant (population, intervention/exposure, comparator, and outcome sufficiently align with NESR protocol), 2) timely (reflects current state of science), 3) transparently documented (methodology and results reported in adequate detail), and 4) high quality (few or no methodological shortcomings based on AMSTAR 2 [A MeaSurement Tool to Assess systematic Reviews]).^a^ However, no eligible existing rapid or systematic reviews were identified.

The protocol for the two rapid reviews conducted as part of this project were registered prospectively on PROSPERO (the International prospective register of systematic reviews; Record ID 346575).

#### Develop inclusion and exclusion criteria

Inclusion and exclusion criteria provide an objective, consistent, and transparent framework for determining which articles to include in each review. NESR analysts worked jointly with the OPS staff to establish inclusion and exclusion criteria that were tailored to the specific review questions addressed. These criteria were developed before any studies were reviewed to guide selection of the most relevant and appropriate body of evidence for each review question. To minimize bias, revisions to the criteria after studies were reviewed were discouraged. Revisions to the criteria that occurred after studies were reviewed are documented in this report (see Protocol amendments). Table 2 describes the inclusion and exclusion criteria for Key Question 2 and Table 3 describes the inclusion and exclusion criteria for Key Question 3.

Table 2 Inclusion and exclusion criteria for Key Question 2: What factors are associated with racial and/or ethnic disparities in human milk feeding in the United States?

Category | Inclusion Criteria | Exclusion Criteria
Study design | - All primary study designs | - All secondary study designs, e.g., narrative reviews, systematic reviews, meta-analyses
Data type | - Quantitative; - Qualitative | - NA
Independent variable | - Race and/or ethnicity (including groups comprised of more than one racial and/or ethnic category) | - Studies that do not state the race or ethnicity of included participants
Comparator | - Different race(s) and/or ethnicity(ies) (including groups comprised of more than one racial and/or ethnic category); Qualitative only:; - No comparator | Quantitative only:; - No comparator
Outcomes | - Human milk feeding initiation rate; - Human milk feeding duration:; ○ Average duration; ○ Rate at a point in time; - Exclusive human milk feeding duration:; ○ Average duration; ○ Rate at a point in time; - Meeting human milk feeding goals; Qualitative only:; - Human milk feeding experiences | - NA
Factors of interest | Quantitative only:; - Factors examined as mediators or moderators of the association between race and/or ethnicity and:; ○ Human milk feeding initiation; ○ Human milk feeding duration; ○ Exclusive human milk feeding duration; ○ Meeting human milk feeding goals; Qualitative only:; - Factors identified or discussed as variables or themes involved in the relationship between race and/or ethnicity and:; ○ Human milk feeding initiation; ○ Human milk feeding duration; ○ Exclusive human milk feeding duration; ○ Meeting human milk feeding goals; ○ Human milk feeding experiences | Quantitative only:; - Studies that only look at associations between:; ○ Race and/or ethnicity and factors; ○ Factors and human milk feeding
Publication date | - January 2009 – June 2022 | - Before January 2009, after June 2022
Publication status | - Articles published in peer-reviewed journals | - Grey literature including/such as:; ○ Government and non-government reports; ○ Unpublished data; ○ Unpublished manuscripts; ○ Abstracts; ○ Conference proceedings; ○ Dissertations and theses
Language | - Articles published in English | - Articles published in languages other than English
Country | - United States | - All other countries
Study participants | - Parent-infant dyads; Qualitative only:; - Study participants analyzed by race and/or ethnicity or stratified by race and/or ethnicity in analyses; OR; - Study participants that are predominantly from U.S. racial and/or ethnic minority groups (≥ two-thirds of the sample) | - Non-human participants; - 100% of infants in a neonatal intensive care unit (NICU); Qualitative only:; - Study participants not analyzed by race and/or ethnicity or stratified by race and/or ethnicity in analyses AND < two-thirds of the sample are from U.S. racial and/or ethnic minority groups

Table 3 Inclusion and exclusion criteria for Key Question 3: What interventions, programs, initiatives, and policies impact racial and/or ethnic disparities in human milk feeding in the United States, and do impacts vary across different racial and/or ethnic, socioeconomic, and geographic groups?

Category | Inclusion Criteria | Exclusion Criteria
Study design | - All primary study designs | - All secondary study designs, e.g., narrative reviews, systematic reviews, meta-analyses
Data type | - Quantitative | - Qualitative
Study participants | - Parent-infant dyads, with:; ○ Study participants analyzed by race and/or ethnicity or stratified by race and/or ethnicity in analyses; OR; ○ Study participants that are predominantly from U.S. racial and/or ethnic minority groups (≥ two-thirds of the sample) | - Non-human participants; - Study participants not analyzed by race and/or ethnicity or stratified by race and/or ethnicity in analyses AND < two-thirds of the sample are from U.S. racial and/or ethnic minority groups; - 100% of infants in a neonatal intensive care unit (NICU)
Intervention/Exposure | - Interventions, programs, initiatives, and/or policies delivered during pregnancy and/or the postpartum period that address human milk feeding | - Exposures and/or factors that are not interventions, programs, initiatives, or policies (e.g., SES, marital status, self-reported social support)
Comparator | - Different interventions, programs, initiatives, and/or policies delivered during pregnancy and/or the postpartum period that address human milk feeding; - No intervention; standard of care; or usual care | - No comparator
Outcomes | - Human milk feeding initiation rate; - Human milk feeding duration:; ○ Average duration; ○ Rate at a point in time; - Exclusive human milk feeding duration:; ○ Average duration; ○ Rate at a point in time; - Meeting human milk feeding goals | - NA
Publication date | - January 2009 – June 2022 | - Before January 2009, after June 2022
Publication status | - Articles published in peer-reviewed journals | - Grey literature, including:; ○ Government and non-government reports; ○ Unpublished data; ○ Unpublished manuscripts; ○ Abstracts; ○ Conference proceedings; ○ Dissertations and theses
Language | - Articles published in English | - Articles published in languages other than English
Country | - United States | - All other countries

#### Search for and select studies

##### Develop the literature search

NESR analysts helped to identify initial key terms and/or relevant articles to ensure that the NESR librarian understood the scope and intent of the rapid review questions. The NESR librarian developed comprehensive electronic bibliographic database searches (January 2009 – June 2022) based on the analytic framework and inclusion and exclusion criteria in PubMed (MEDLINE), Web of Science, and CINAHL. Because of the similarity in concepts between Key Question 2 and Key Question 3, a single search strategy was used to identify articles for both questions. The search strategy was designed to limit results by language (English), population (human), date (January 2009 – June 2022), and publication type (e.g., to filter out news, editorials, and comments).

The search strategy was tested and underwent multiple revisions to preview results, correct any syntax, spelling, or grammatical errors, and to refine and adjust the search before it was finalized for use. As a time-savings concession, the search strategies for these rapid reviews were not peer-reviewed by a second librarian. The full search strategy is available in Appendix 2.

After finalizing the search strategies, the NESR librarian conducted all of the searches. The NESR librarian electronically eliminated duplicate records at the search level using a citation management program (EndNote 20; Clarivate Analytics, Philadelphia, PA). Additional duplicates identified by NESR analysts during screening were also removed from the search results. Because some journals publish articles electronically in advance of the print journal, the search may have captured these articles, and they were eligible for inclusion in the review, even though there is a possibility that they were assigned an official publication date outside the window of the search date range. The NESR librarian documented the total number of unique articles identified, indicating how many were identified from each database searched. This documentation includes the total, raw search results, as well as search results after removal of duplicates.

##### Screen the literature search results

NESR analysts screened all literature search results at three levels: title, abstract, and full-text. The goal of screening was to review the search results and exclude those that did not meet the inclusion criteria. The first level of screening was completed using only the title of each article. If an article was not excluded at this level, it moved forward to the second level, where the abstract was screened. If an article was not excluded after reviewing the abstract, it moved to the third level, where the full text of the article was screened. Any disagreements at the full text level between analysts was reconciled. If necessary, a third analyst was consulted to resolve differences.

The screening of search results was facilitated using a web-based tool (DistillerSR, DistillerSR Inc., Ottawa, Ontario, Canada) and screening forms that were developed based on the inclusion and exclusion criteria identified for each rapid review question. A re-ranking function was utilized in DistillerSR to reorder articles by relevancy. At the title and abstract levels, one analyst screened 100 percent of records, and a second analyst dual screened 30 percent of records. Articles that were included by one or more analysts were included without verification to the next level of screening. At the full-text level, one analyst screened 100 percent of records and a second analyst verified all include and exclude decisions. A hand search, in which an analyst systematically searches the reference sections of included articles, was not conducted.

If multiple articles were identified that effectively presented the same data from the same study or cohort, the article that most directly addressed the review question was included to avoid duplicative data. However, if the articles addressed unique data related to the question or were needed to comprehensively present information from a study or cohort, then all articles were included. Included articles from the same study or cohort are noted in the review, and this was taken into consideration when weighing the amount of evidence to answer a question.

##### Document the search results

After the electronic searches and screening processes were completed, NESR analysts and the librarian documented the literature search and screening results by compiling lists of the included and excluded citations, along with the rationale for exclusion at the full-text level.

#### Extract data and assess the risk of bias

NESR analysts extracted and summarized data from each included article to objectively describe the body of evidence available to answer each rapid review question. For quantitative articles included in the rapid review, NESR analysts assessed the risk of bias. Risk of bias assessments were not completed for qualitative articles included in the rapid review due to time constraints and the exploratory nature of this section of the review. The extracted data and assessment of risk of bias were used to populate evidence tables to present the key data used in the synthesis for the review.

##### Extract data

To expedite data extraction, only the most essential data for answering the question were extracted. For the rapid reviews, information on the following elements were extracted: study design; sample size (N); population description; analysis type (e.g., mediation, path analysis, moderation, interaction, thematic); factors assessed; intervention, program, initiative, and/or policy assessed; race and ethnicity category components and information on how race and ethnicity was examined^a^,^b^; outcomes; and results.

a Martinez RAM, Andrabi N, Goodwin AN, Wilbur RE, Smith NR, Zivich PN. Resource Packet for “Clear communication of race and ethnicity for public health: best practices & common failings”. 2021. doi: 10.17615/dcfj-9g46

b Information on how race and ethnicity was examined is presented in Appendix 3

Once the types of data to be extracted were determined, a data extraction form was developed and used to facilitate accurate, consistent, and efficient data extraction. This form ensured that the same information from each article was formatted consistently, which makes the content easier to compare and contrast during synthesis. NESR analysts used Microsoft Excel to extract data.

One NESR analyst extracted data from each included article using the data extraction form. In some cases, the required data was not reported in the article. In those situations, the data was recorded as “not reported.” However, if the required data were reported in an article’s protocol or related publication, the analyst extracted the data and noted the publication from which it was extracted. Next, a second analyst reviewed only the extracted results for completeness, accuracy, and consistent presentation and formatting. Any disagreements were reconciled between analysts. Evidence tables were created by NESR analysts using the extracted data.

##### Assess risk of bias

Each quantitative article included in the rapid reviews underwent a formal risk of bias assessment. Risk of bias assessments were not completed for qualitative articles. Risk of bias is the likelihood of a systematic error or deviation from the truth, in results or interferences, which can lead to underestimation or overestimation of either the true effect of an intervention on an outcome or the true association between an exposure and outcome.

NESR assessed the risk of bias of randomized controlled trials (RCT), including parallel group trials, cluster-randomized trials, and cross-over trials, using version 2 of the Cochrane tool for assessing risk of bias in randomised trials (RoB 2.0).^c^ NESR assessed the risk of bias of non-RCT and quasi-experimental studies using the Risk Of Bias In Non-randomised Studies – of Interventions (ROBINS-I).^d^ NESR assessed the risk of bias of observational studies that were not quasi-experimental using the NESR Risk of Bias for Nutrition Observational Studies tool (RoB-NObs).^e^ For each quantitative article included in the rapid reviews, one NESR analyst completed the risk of bias tool appropriate for the study’s design and the assessment was verified by a second analyst. Analysts answered the signaling questions based only on the data that was extracted for the rapid review for a specific result and determined domain-level risk of bias judgements (e.g., Low, Moderate, Serious, Critical). If necessary, analysts referred to previous and/or related publications to obtain information to complete items in the tool. The analysts reconciled disagreements and if a disagreement could not be resolved by the two analysts, a third NESR analyst was asked to provide a third-party consultation.

c Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ. 2019:366:l4898. doi: 10.1136/bmj.l4898.31462531

d Sterne JAC, Hernán MA, Reeves BC, . ROBINS-I: a tool for assessing risk of bias in nonrandomised studies of interventions. BMJ. 2016;355:i4919. doi:10.1136/bmj.i4919.27733354

e “Risk of Bias for Nutrition Observational Studies” tool (RoB-NObs) ( Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC. )

Note, the purpose of the quantitative studies in Key Question 2 is to identify factors that may mediate or moderate the relationship between race and/or ethnicity and human milk feeding outcomes and is, therefore, exploratory in nature. Without knowledge of the factors that would be identified during the review ahead of time, specifying the most appropriate key confounders that would be applicable to all factors was not feasible. For this reason, risk of bias due to confounding was not assessed for Key Question 2 using the risk of bias tools. However, because the relationships under study in Key Question 2 are at risk of bias due to confounding, information on the variables controlled for (in addition to the variables assessed as mediators or moderators) in each individual paper was extracted and reported in the data table.

The results of each risk of bias assessment are displayed in risk of bias tables. These tables provide transparency to the domain-level risk of bias judgements for each included article using a color-coded system. Limitations identified during risk of bias assessments are described and considered in the synthesis.

#### Synthesize the evidence

Evidence synthesis was conducted by describing, comparing and contrasting, and combining data from multiple studies qualitatively, or narratively, to answer the review question. The synthesis of the body of evidence involved identifying overarching themes or key concepts from the findings, identifying and explaining similarities and differences between studies, and determining whether certain factors may have affected the relationships being examined. Evidence synthesis conducted as part of the rapid reviews in this project aligns with that of NESR systematic reviews but was more concise.

The National Institute on Minority Health and Health Disparities (NIMHD) research framework^a^ was used to organize the syntheses (Appendix 4). This framework was chosen in order to present the results in the context of the multi-dimensional nature of human milk feeding disparities. The NIMHD research framework combines two dimensions to categorize and assess health determinants: levels of influence (individual, interpersonal, community, societal) and domains of influence (biological, behavioral, physical/built environment, sociocultural environment, health care system). For both Key Question 2 and Key Question 3, evidence was synthesized for each combination of level and domain of influence.

a Alvidrez J, Castille D, Laude-Sharp M, Rosario A, Tabor D. The National Institute on Minority Health and Health Disparities research framework. Am J Public Health. 2019;109:S16–S20. doi:10.2105/AJPH.2018.304883 30699025

NESR analysts drafted a description of the studies included in the review to begin the process of synthesizing the evidence using analytic frameworks (see Table 4 and Table 5) to guide how the evidence was organized and described. Next, NESR analysts reviewed the included articles individually, and the body of evidence collectively. Patterns of agreement and disagreement among the findings were examined, and methodological differences between the studies were assessed to potentially help explain disagreement. Gaps in the body of evidence were also identified.

Table 4 Analytic framework for Key Question 2: What factors are associated with racial and/or ethnic disparities in human milk feeding in the United States?

Population | Study Type | Factors of Interest | Independent Variable | Comparator | Outcomes
Parent-infant dyads in the U.S. | Quantitative Studies | Factors examined as mediators or moderators of the association between race and/or ethnicity and human milk feeding outcomes | Race and/or ethnicity | Different race and/or ethnicity | Human milk feeding initiation; Human milk feeding duration; Exclusive human milk feeding duration; Meeting human milk feeding goals
Parent-infant dyads in the U.S. | Qualitative Studies | Factors identified or discussed as variables or themes involved in the relationship between race and/or ethnicity and human milk feeding outcomes | Race and/or ethnicity | Different race and/or ethnicity; No comparator | Human milk feeding initiation; Human milk feeding duration; Exclusive human milk feeding duration; Meeting human milk feeding goals; Human milk feeding experiences

The evidence for Key Question 2 was organized using the following structure:

- Factors of Interest - NIMHD Level of Influence: Societal, Community, Interpersonal, Individual
  ○ Factors of Interest - NIMHD Domain of Influence: Biological, Behavioral, Physical/Built Environment, Sociocultural Environment, Health Care System

Table 5 Analytic framework for Key Question 3: What interventions, programs, initiatives, and policies impact racial and ethnic disparities in human milk feeding in the United States, and do impacts vary across different racial and/or ethnic, socioeconomic, and geographic groups?

Population | Interventions/Exposures | Comparators | Outcomes | Key confounders
Parent-infant dyads in the U.S., with:; Study participants analyzed by race and/or ethnicity or stratified by race and/or ethnicity in analyses; OR; Study participants that are predominantly from U.S. racial and/or ethnic minority groups (≥ two-thirds of the sample) | Interventions, programs, initiatives, and/or policies delivered during pregnancy and/or the postpartum period that address human milk feeding | Different interventions, programs, initiatives, and/or policies; No intervention; standard of care; or usual care | Human milk feeding initiation; Human milk feeding duration; Exclusive human milk feeding duration; Meeting human milk feeding goals | Family structure; Parental age; Parity; Socioeconomic status (SES)

The evidence for Key Question 3 was organized using the following structure:

- Intervention/Exposure - NIMHD Level of Influence: Societal, Community, Interpersonal, Individual
  ○ Intervention/Exposure - NIMHD Domain of Influence: Biological, Behavioral, Physical/Built Environment, Sociocultural Environment, Health Care System

The following was considered in the synthesis of quantitative data for Key Question 2 and Key Question 3: study design, associations between the factors identified and race and/or ethnicity and human milk feeding outcomes, along with considerations for assessing the body of evidence (risk of bias, consistency, directness, precision, and generalizability). Additionally, the synthesis of quantitative data for Key Question 3 specifically examined whether certain interventions, programs, initiatives, and/or policies were more successful at reducing racial and/or ethnic disparities in human milk feeding in certain racial and/or ethnic, socioeconomic, or geographic groups. This aspect of Key Question 3 was addressed by examining the results of studies that compare the impact of interventions, programs, initiatives, and policies between different racial and/or ethnic, socioeconomic, or geographic groups and the results of studies that investigate the same or similar interventions, programs, initiatives, and/or policies, but were conducted in different racial and/or ethnic, socioeconomic, or geographic groups.

The following were considered in the synthesis of qualitative data for Key Question 2: study design and identification of variables or themes related to race and/or ethnicity and human milk feeding outcomes.

#### Develop summary statements

NESR analysts developed summary statements outlining the main themes from the synthesis. Because modifications were made to NESR’s standard systematic review methods and these reviews included limited technical expert involvement, conclusion statements and grades were not developed to answer the research questions. However, the grading elements (i.e., risk of bias, consistency, precision, directness, generalizability) were referenced to assess the evidence, determine limitations, and inform the development of summary statements. Additionally, summary statements were not developed for qualitative studies for Key Question 2 due to the exploratory nature of qualitative articles and the lack of statistical comparisons between racial and/or ethnic groups.

#### Recommend future research

Research gaps and methodological limitations identified during data extraction, synthesis, and discussions with the OPS team were documented and included in the report for each question. They are framed as research recommendations that detail areas where further research is needed to strengthen the body of evidence on the research question of interest.

#### Protocol amendments

Amendments to the rapid review protocols after the commencement of screening are documented in Table 6.

Table 6 Protocol amendments

Date | Protocol change | Description
August 2022 | Exclusion of qualitative studies that did not analyze or stratify analyses by race and/or ethnicity AND < two-thirds of the sample are from U.S. racial and/or ethnic minority groups (Key Question 2) | Inclusion and exclusion criteria added to ensure focus of included qualitative articles was on racially and/or ethnically diverse parent-infant dyads in the United States. Update made during screening.
August 2022 | Exclusion of studies where 100% of infants are hospitalized in the NICU (Key Questions 2 and 3) | Criteria added to focus review on population that is more broadly generalizable to parent-infant dyads in the United States. Update made during screening.
September 2022 | Exclusion of grey literature search (Key Questions 2 and 3) | Grey literature search was not pursued as a time savings concession due to the large volume of included articles from the database search. Update made during screening.