# Acknowledgments and funding

The NESR project team developed the protocol for examining the scientific evidence, including the inclusion and exclusion criteria; reviewed all studies that met the set criteria; described and synthesized the body of evidence for each question; and wrote the summary statements.

The NESR project team worked with the review sponsors, the OPS Supplemental Nutrition and Safety Research and Analysis Division (SNAS-RAD) team, to determine the scope of the questions and to develop the rapid review protocol:

- Carol Dreibelbis, MPH
- Ruth Morgan, MPH
- Amanda Reat, PhD, RD
- Kelley Scanlon, PhD, RD (through August 2022)

The NESR project team thanks:

- Darcy Güngör, MS (Systematic Review Analyst, NESR team; Panum Group, LLC, under contract with the FNS, USDA – through May 2022) for her contributions to protocol development
- Laural English, PhD, Brittany Kingshipp, PhD, Ramkripa Raghavan, DrPH, MPH, MSc, Joanne Spahn, MS, RD (all NESR Branch, NGAD, CNPP, FNS, USDA) for their contributions to data extraction
- Natasha Cole, PhD, MPH, RD, Julie Nevins, PhD, Sara Scinto-Madonich, MS, (all NESR Branch, NGAD, CNPP, FNS, USDA) and Julie Obbagy, PhD, RD (NESR Branch Chief, NGAD, CNPP, FNS, USDA) for their contributions to data extraction and review of earlier versions of this report