# Appendix 7 Evidence table for qualitative themes involved in human milk feeding (Key Question 2)

Table A-10 Studies that examined factors identified or discussed as variables or themes involved in human milk feeding outcomes (Key Question 2)^*^