# Appendix 6 Evidence table for quantitative factors associated with racial and/or ethnic disparities in human milk feeding (Key Question 2)

Table A-9 Results of studies that examined whether certain factors mediated or moderated the relationship between race and/or ethnicity and human milk feeding outcomes (Key Question 2)^*^