# Appendix 5 Excluded articles

The following table (Table A-8) lists the articles excluded after full-text screening for these rapid reviews. At least one reason for exclusion is provided for each article, though this may not reflect all possible reasons. Information about articles excluded after title and abstract screening is available upon request.

Table A-8 Articles excluded after full-text screening^*^

| Citations | Reason(s) for exclusion
1 | Aaronson, ACB. Mode of Delivery and Maternal and Infant Risk Factors and Health Outcomes. University of California, San Francisco; 2011. | Publication status
2 | Abbott, J, Carty, J, Batig, AL. Infant Feeding Practices, Workplace Breastfeeding/Lactation Practices, and Perception of Unit/Service Support Among Primiparous Active Duty Servicewomen. Mil Med. 2019. 184:e315-e320. doi:10.1093/milmed/usy356. | Intervention/exposure - KQ3; Independent variable - KQ2
3 | Abdulloeva, S, Eyler, AA. Policies on worksite lactation support within states and organizations. J Womens Health (Larchmt). 2013. 22:769-74. doi:10.1089/jwh.2012.4186. | Mediators/moderators; Comparator - KQ3
4 | Abeling, BA. Organizational Factors, Cesarean Rates, & Exclusive Breastfeeding among Women with a Prior Cesarean Birth. University of California, Davis; 2017. | Publication status
5 | Adams Hillard, PJ. Racial Disparities And Support For Breastfeeding. Contemporary OB/GYN. 2014. 59:44-44. | Mediators/moderators; Intervention/exposure - KQ3
6 | Adesoye, T, Mangurian, C, Choo, EK, Girgis, C, Sabry-Elnaggar, H, Linos, E. Perceived Discrimination Experienced by Physician Mothers and Desired Workplace Changes: A Cross-sectional Survey. JAMA Intern Med. 2017. 177:1033-1036. doi:10.1001/jamainternmed.2017.1394. | Mediators/moderators; Intervention/exposure - KQ3; Study participants
7 | Aguayo, L, Olave-Pichon, A, Ariza, AJ, Binns, HJ. Characteristics of Very Young Hispanic Children Referred for Obesity Management. Glob Pediatr Health. 2017. 4:2333794x17739192. doi:10.1177/2333794x17739192. | Mediators/moderators; Intervention/exposure - KQ3
8 | Aguila Gonzalez, AI, Henao, MM, Ahlers-Schmidt, CR. Collaborating with Culturally Competent Prenatal Education among Hispanic Communities. Kans J Med. 2022. 15:1-7. doi:10.17161/kjm.vol15.15613. | Outcome
9 | Ahlers-Schmidt, CR, Schunn, C, Engel, M, Dowling, J, Neufeld, K, Kuhlmann, S. Implementation of a Statewide Program to Promote Safe Sleep, Breastfeeding and Tobacco Cessation to High Risk Pregnant Women. J Community Health. 2019. 44:185-191. doi:10.1007/s10900-018-0571-4. | Outcome
10 | Ahluwalia, IB, D’Angelo, D, Morrow, B, McDonald, JA. Association between acculturation and breastfeeding among Hispanic women: data from the Pregnancy Risk Assessment and Monitoring System. J Hum Lact. 2012. 28:167-73. doi:10.1177/0890334412438403. | Intervention/exposure - KQ3; Comparator - KQ2
11 | Ahluwalia, IB, Li, R, Morrow, B. Breastfeeding practices: does method of delivery matter?. Matern Child Health J. 2012. 16 Suppl 2:231-7. doi:10.1007/s10995-012-1093-9. | Mediators/moderators; Intervention/exposure - KQ3
12 | Ahmed, AH, Rojjanasrirat, W. Breastfeeding Outcomes, Self-Efficacy, and Satisfaction Among Low-Income Women With Late-Preterm, Early-Term, and Full-Term Infants. J Obstet Gynecol Neonatal Nurs. 2021. 50:583-596. doi:10.1016/j.jogn.2021.06.010. | Intervention/exposure - KQ3; Independent variable - KQ2
13 | Alakaam, A, Lemacks, J, Yadrick, K, Connell, C, Choi, HW, Newman, RG. Breastfeeding Practices and Barriers to Implementing the Ten Steps to Successful Breastfeeding in Mississippi Hospitals. J Hum Lact. 2018. 34:322-330. doi:10.1177/0890334417737294. | Outcome
14 | Alakaam, A. Demand for Lactation Leads to Flowing Supply of Success: Support Requested from States to Improve Breastfeeding Practices. J Midwifery Womens Health. 2019. 64:699-702. doi:10.1111/jmwh.12977. | Study design
15 | Alb, CH, Theall, K, Jacobs, MB, Bales, A. Awareness of United States’ Law for Nursing Mothers among Employers in New Orleans, Louisiana. Womens Health Issues. 2017. 27:14-20. doi:10.1016/j.whi.2016.10.009. | Study participants
16 | Albuquerque Frota, M, Freitas Casimiro, C, de Oliveira Bastos, P, Albuquerque Sousa Filho, O, Cavalcante Martins, M, Soares Gondim, AP. Mothers’ knowledge concerning breastfeeding and complementation food: an exploratory study. Online Brazilian Journal of Nursing. 2013. 12:1-1. doi:10.5935/1676-4285.20133890. | Country
17 | Alexander, A, O’Riordan, MA, Furman, L. Do breastfeeding intentions of pregnant inner-city teens and adult women differ?. Breastfeed Med. 2010. 5:289-96. doi:10.1089/bfm.2009.0083. | Outcome
18 | Al-Faraj, AO, Pandey, S, Herlihy, MM, Pang, TD. Factors affecting breastfeeding in women with epilepsy. Epilepsia. 2021. 62:2171-2179. doi:10.1111/epi.17003. | Study design
19 | Alghamdi, S, Horodynski, M, Stommel, M. Racial and ethnic differences in breastfeeding, maternal knowledge, and self-efficacy among low-income mothers. Appl Nurs Res. 2017. 37:24-27. doi:10.1016/j.apnr.2017.07.009. | Mediators/moderators; Intervention/exposure - KQ3
20 | Al-Kandari, Yagoub, Ahmed, RamadanA. Social, psychological and demographic variables related to breast-feeding among Kuwaiti mothers. Eastern Mediterranean Health Journal. 2018. 24:624-630. doi:10.26719/2018.24.7.624. | Country
21 | Allen, D, Baker, B. Supporting Mothering Through Breastfeeding for Incarcerated Women. JOGNN: Journal of Obstetric, Gynecologic & Neonatal Nursing. 2013. 42:S103-S103. doi:10.1111/1552-6909.12203. | Publication status
22 | Allen, M, Schafer, DJ. Nurses Improving the Health of Mothers and Infants by Dancing the 10 Steps to Successful Breastfeeding…Proceedings of the 2015 AWHONN Convention. JOGNN: Journal of Obstetric, Gynecologic & Neonatal Nursing. 2015. 44:S52-S52. doi:10.1111/1552-6909.12613. | Publication status
23 | Allers, KS. The False and the Furious: Countering Misinformation and Negative Messaging in Breastfeeding Support. Clinical Lactation. 2018. 9:164-170. doi:10.1891/2158-0782.9.4.164. | Study design
24 | Almeida, H, Venancio, SI, Sanches, MT, Onuki, D. The impact of kangaroo care on exclusive breastfeeding in low birth weight newborns. J Pediatr (Rio J). 2010. 86:250-3. doi:10.2223/jped.1974. | Country
25 | Almeida, R, Alvarez Gutierrez, S, Whaley, SE, Ventura, AK. A Qualitative Study of Breastfeeding and Formula-Feeding Mothers’ Perceptions of and Experiences in WIC. J Nutr Educ Behav. 2020. 52:615-625. doi:10.1016/j.jneb.2019.12.006. | Mediators/moderators; Intervention/exposure - KQ3
26 | Almeida, R, Gutierrez, SA, Whaley, SE, Ventura, AK. A Qualitative Study of Breastfeeding and Formula -Feeding Mothers? Perceptions of and Experiences in WIC. Journal of Nutrition Education and Behavior. 2020. 52:615-625. doi:10.1016/j.jneb.2019.12.006. | Intervention/exposure - KQ3; Independent variable - KQ2
27 | Altindag, O, Joyce, TJ, Reeder, JA. Can Nonexperimental Methods Provide Unbiased Estimates of a Breastfeeding Intervention? A Within-Study Comparison of Peer Counseling in Oregon. Eval Rev. 2019. 43:152-188. doi:10.1177/0193841x19865963. | Mediators/moderators; Study participants
28 | Alvarez, R, Serwint, JR, Levine, DM, Bertram, A, Sattari, M. Lawyer mothers: infant-feeding intentions and behavior. South Med J. 2015. 108:262-7. doi:10.14423/smj.0000000000000277. | Intervention/exposure - KQ3; Independent variable - KQ2
29 | Alves, VGS, Mota, MC, Pagliari, C. Sociodemographic Characteristics Related To Knowing The Benefits Of Breastfeeding. Rev Paul Pediatr. 2021. 39:e2020101. doi:10.1590/1984-0462/2021/39/2020101. | Country
30 | Ambikapathi, R, Kosek, MN, Lee, GO, Mahopo, C, Patil, CL, Maciel, BL, Turab, A, Islam, MM, Ulak, M, Bose, A, Paredes Olortegui, M, Pendergast, LL, Murray-Kolb, LE, Lang, D, McCormick, BJ, Caulfield, LE. How multiple episodes of exclusive breastfeeding impact estimates of exclusive breastfeeding duration: report from the eight-site MAL-ED birth cohort study. Matern Child Nutr. 2016. 12:740-56. doi:10.1111/mcn.12352. | Country
31 | Ames, EG, Burrows, HL. Differing Experiences with Breastfeeding in Residency Between Mothers and Coresidents. Breastfeed Med. 2019. 14:575-579. doi:10.1089/bfm.2019.0001. | Independent variable - KQ2; Study participants
32 | Amir, LH. Breastfeeding in public: “You can do it?”. Int Breastfeed J. 2014. 9:187. doi:10.1186/s13006-014-0026-1. | Independent variable - KQ2; Outcome
33 | Andaya, E, Bonuck, K, Barnett, J, Lischewski-Goel, J. Perceptions of primary care-based breastfeeding promotion interventions: qualitative analysis of randomized controlled trial participant interviews. Breastfeed Med. 2012. 7:417-22. doi:10.1089/bfm.2011.0151. | Outcome
34 | Anderson, AK, Johnson, E, Motoyasu, N, Bignell, WE. Awareness of Breastfeeding Laws and Provisions of Students and Employees of Institutions of Higher Learning in Georgia. J Hum Lact. 2019. 35:323-339. doi:10.1177/0890334418801536. | Outcome
35 | Anderson, J, Kuehl, RA, Drury, SA, Tschetter, L, Schwaegerl, M, Hildreth, M, Bachman, C, Gullickson, H, Yoder, J, Lamp, J. Policies aren’t enough: the importance of interpersonal communication about workplace breastfeeding support. J Hum Lact. 2015. 31:260-6. doi:10.1177/0890334415570059. | Independent variable - KQ2; Study participants
36 | Anderson, J, Kuehl, RA, Drury, Mehltretter SA, Tschetter, L, Schwaegerl, M, Hildreth, M, Bachman, C, Gullickson, H, Yoder, J, Lamp, J. Policies Aren’t Enough: The Importance of Interpersonal Communication about Workplace Breastfeeding Support. Journal of Human Lactation. 2015. 31:260-266. doi:10.1177/0890334415570059. | Study participants
37 | Andrew, N, Harvey, K. Infant feeding choices: experience, self-identity and lifestyle. Matern Child Nutr. 2011. 7:48-60. doi:10.1111/j.1740-8709.2009.00222.x. | Country
38 | Andrews, EE, Powell, RM, Ayers, KB. Experiences of Breastfeeding among Disabled Women. Womens Health Issues. 2021. 31:82-89. doi:10.1016/j.whi.2020.09.001. | Intervention/exposure - KQ3; Independent variable - KQ2
39 | Angeletti, MA, Llossas, JR. Workplace Lactation Programs in Small WIC Service Sites: A Potential Model. J Nutr Educ Behav. 2018. 50:307-310.e1. doi:10.1016/j.jneb.2017.10.001. | Outcome
40 | Angeletti, MA. Breastfeeding mothers returning to work: possibilities for information, anticipatory guidance and support from US health care professionals. J Hum Lact. 2009. 25:226-32. doi:10.1177/0890334408329482. | Study design
41 | Annagür, Ali, Annagür, Bilge Burçak, Sahin, Akkiz, Ors, Rahmi, Kara, Fatih. Is maternal depressive symptomatology effective on success of exclusive breastfeeding during postpartum 6 weeks?. Breastfeeding Medicine. 2013. 8:53-57. doi:10.1089/bfm.2012.0036. | Country
42 | Anstey, EH, MacGowan, CA, Allen, JA. Five-Year Progress Update on the Surgeon General’s Call to Action to Support Breastfeeding, 2011. Journal of Women’s Health (15409996). 2016. 25:768-776. doi:10.1089/jwh.2016.5990. | Study design
43 | Antoñanzas-Baztán, E, Belintxon, M, Marín-Fernández, B, Redín-Areta, MD, Mujika, A, Pumar-Méndez, MJ, Lopez-Dicastillo, O. Six-month breastfeeding maintenance after a self-efficacy promoting programme: an exploratory trial. Scand J Caring Sci. 2021. 35:548-558. doi:10.1111/scs.12870. | Country
44 | Apostolakis-Kyrus, K, Valentine, C, DeFranco, E. Factors associated with breastfeeding initiation in adolescent mothers. J Pediatr. 2013. 163:1489-94. doi:10.1016/j.jpeds.2013.06.027. | Mediators/moderators; Intervention/exposure - KQ3
45 | Aquilina, S. The relationship between self-efficacy and breastfeeding duration. Carlow University; 2011. | Publication status
46 | Aquino, LM, Newcomb, P, True, B, Hoff, T, Gentile, D, Patton, L, Raquepo, F, Cash, E. Cross-Sectional Study of Influences on Maternal Decisions Regarding Feeding Premature and Ill Neonates. J Perinat Neonatal Nurs. 2022. 36:209-217. doi:10.1097/jpn.0000000000000553. | Mediators/moderators; Intervention/exposure - KQ3
47 | Arcain Nass, EM, Silva Marcon, S, Ferraz Teston, E, Viccentine Coutinho Monteschio, L, dos Reis, P, de Lima Vieira, VC. Maternal Factors And Early Weaning From Exclusive Breastfeeding. Revista de Pesquisa: Cuidado e Fundamental. 2021. 13:1698-1703. doi:10.9789/2175-5361.rpcfo.v13.10614. | Country
48 | Arevalo-Marcano, S, Buyukgoz, C, Zia, M, Rajegowda, B. Prevalence Of Maternal Marijuana Use And Its Effects On Neonatal Growth And Breastfeeding In An Urban ‘Babyfriendly’ Hospital. Neonatal Intensive Care. 2019. 32:16-19. | Outcome
49 | Arias, MP, Wang, E, Leitner, K, Sannah, T, Keegan, M, Delferro, J, Iluore, C, Arimoro, F, Streaty, T, Hamm, RF. The impact on postpartum care by telehealth: a retrospective cohort study. Am J Obstet Gynecol MFM. 2022. 4:100611. doi:10.1016/j.ajogmf.2022.100611. | Mediators/moderators; Intervention/exposure - KQ3
50 | Aris, IM, Bernard, JY, Chen, LW, Tint, MT, Pang, WW, Lim, WY, Soh, SE, Saw, SM, Godfrey, KM, Gluckman, PD, Chong, YS, Yap, F, Kramer, MS, Lee, YS. Infant body mass index peak and early childhood cardio-metabolic risk markers in a multi-ethnic Asian birth cohort. Int J Epidemiol. 2017. 46:513-525. doi:10.1093/ije/dyw232. | Country
51 | Artzi-Medvedik, R, Haile, ZT, Chertok, IRA. Association Between Influenza Vaccination During Pregnancy and Breastfeeding Duration. Breastfeed Med. 2022. 17:484-492. doi:10.1089/bfm.2022.0001. | Mediators/moderators; Intervention/exposure - KQ3
52 | Ashida, S, Lynn, FB, Williams, NA, Schafer, EJ. Competing infant feeding information in mothers’ networks: advice that supports v. undermines clinical recommendations. Public Health Nutr. 2016. 19:1200-10. doi:10.1017/s1368980015002220. | Mediators/moderators; Intervention/exposure - KQ3
53 | Asiodu, I, Flaskerud, JH. Got milk? A look at breastfeeding from an African American perspective. Issues Ment Health Nurs. 2011. 32:544-6. doi:10.3109/01612840.2010.544842. | Study design
54 | Asiodu, IV. Identifying barriers and facilitators to breastfeeding initiation in the African American community. University of California, San Francisco; 2014. | Publication status
55 | Asiodu, IV, Beal, L, Sufrin, C. Breastfeeding in Incarcerated Settings in the United States: A National Survey of Frequency and Policies. Breastfeeding Medicine. 2021. 16:710-716. doi:10.1089/bfm.2020.0410. | Independent variable - KQ2; Study participants
56 | Asiodu, IV, Bugg, K, Palmquist, AEL. Achieving Breastfeeding Equity and Justice in Black Communities: Past, Present, and Future. Breastfeed Med. 2021. 16:447-451. doi:10.1089/bfm.2020.0314. | Study design
57 | Assibey-Mensah, V, Suter, B, Thevenet-Morrison, K, Widanka, H, Edmunds, L, Sekhobo, J, Dozier, A. Effectiveness of Peer Counselor Support on Breastfeeding Outcomes in WIC-Enrolled Women. J Nutr Educ Behav. 2019. 51:650-657. doi:10.1016/j.jneb.2019.03.005. | Mediators/moderators; Intervention/exposure - KQ3
58 | Astuti, AW, Kurniawati, HF, Kurniawati, HF. A Qualitative Study on the Breastfeeding Experiences of Young Mothers. Nurse Media Journal of Nursing. 2021. 11:35-49. doi:10.14710/nmjn.v11i1.33539. | Country
59 | Atabay, E, Moreno, G, Nandi, A, Kranz, G, Vincent, I, Assi, TM, Winfrey, EM, Earle, A, Raub, A, Heymann, SJ. Facilitating working mothers’ ability to breastfeed: global trends in guaranteeing breastfeeding breaks at work, 1995-2014. J Hum Lact. 2015. 31:81-8. doi:10.1177/0890334414554806. | Independent variable - KQ2; Study participants
60 | Attanasio, L, Kozhimannil, KB, McGovern, P, Gjerdingen, D, Johnson, PJ. The impact of prenatal employment on breastfeeding intentions and breastfeeding status at 1 week postpartum. J Hum Lact. 2013. 29:620-8. doi:10.1177/0890334413504149. | Mediators/moderators; Intervention/exposure - KQ3
61 | Au, LE, Gurzo, K, Paolicelli, C, Whaley, SE, Weinfield, NS, Ritchie, LD. Diet Quality of US Infants and Toddlers 7-24 Months Old in the WIC Infant and Toddler Feeding Practices Study-2. J Nutr. 2018. 148:1786-1793. doi:10.1093/jn/nxy192. | Mediators/moderators; Intervention/exposure - KQ3
62 | Auger, SJ, Verbiest, S, Spickard, JV, Simán, FM, Colindres, M. Participatory group prenatal education using photonovels: Evaluation of a lay health educator model with low-income Latinas. J Particip Med. 2015. 7. | Independent variable - KQ2; Outcome
63 | Augustin, AmyL, Donovan, Kathleen, Lozano, EmilyA, Massucci, DianeJ, Wohlgemuth, Fran. Still Nursing at 6 Months: A Survey of Breastfeeding Mothers. MCN: The American Journal of Maternal Child Nursing. 2014. 39:50-55. doi:10.1097/01.NMC.0000437534.99514.dc. | Independent variable - KQ2; Study participants
64 | Austin, D. Researcher Seeks to Bridge Breastfeeding Disparity. Science of Caring. 2017. 2-2. | Study design
65 | Avery, AB, Magnus, JH. Expectant fathers’ and mothers’ perceptions of breastfeeding and formula feeding: a focus group study in three US cities. J Hum Lact. 2011. 27:147-54. doi:10.1177/0890334410395753. | Study participants
66 | Axelsen, VR, Owais, AI, Qian, F, Perigo, CL, Weber-Gasparoni, K. Bedsharing and Oral Health-related Feeding Behaviors Among Zero- to Three-year-old Children. Pediatr Dent. 2016. 38:477-483. | Mediators/moderators; Intervention/exposure - KQ3
67 | Bagga, N, Kurian, S, Mohamed, A, Reddy, P, Chirla, DK. Pasteurized Donor Human Milk Should Not Replace Mother’s Own Milk in Preterm Neonates: A Quality Initiative Toward Decreasing the “PDHM Dependency”. Breastfeed Med. 2022. 17:252-258. doi:10.1089/bfm.2021.0155. | Independent variable - KQ2; Study participants
68 | Bai, Y, Middlestadt, SE, Peng, CY, Fly, AD. Predictors of continuation of exclusive breastfeeding for the first six months of life. J Hum Lact. 2010. 26:26-34. doi:10.1177/0890334409350168. | Intervention/exposure - KQ3; Independent variable - KQ2
69 | Bai, Y, Wunderlich, SM, Fly, AD. Predicting intentions to continue exclusive breastfeeding for 6 months: a comparison among racial/ethnic groups. Matern Child Health J. 2011. 15:1257-64. doi:10.1007/s10995-010-0703-7. | Outcome
70 | Bai, Y, Wunderlich, SM. Lactation accommodation in the workplace and duration of exclusive breastfeeding. J Midwifery Womens Health. 2013. 58:690-6. doi:10.1111/jmwh.12072. | Study participants
71 | Bai, YK, Dinour, LM, Pope, GA. Determinants of the Intention to Pump Breast Milk on a University Campus. J Midwifery Womens Health. 2016. 61:563-570. doi:10.1111/jmwh.12488. | Outcome
72 | Bai, YK, Wunderlich, SM, Weinstock, M. Employers’ readiness for the mother-friendly workplace: an elicitation study. Matern Child Nutr. 2012. 8:483-91. doi:10.1111/j.1740-8709.2011.00334.x. | Outcome
73 | Bailey, BA, Wright, HN. Breastfeeding initiation in a rural sample: predictive factors and the role of smoking. J Hum Lact. 2011. 27:33-40. doi:10.1177/0890334410386955. | Intervention/exposure - KQ3; Independent variable - KQ2
74 | Bailey, C. Breastfeeding mothers’ experiences of bedsharing: A qualitative study. Breastfeed Rev. 2016. 24:33-40. | Country
75 | Bailey, RL, Jun, S, Eldridge, AL. The 2016 Feeding Infants and Toddlers Study (FITS): Dietary Intakes and Practices of Children in the United States from Birth to 48 Months. Nestle Nutr Inst Workshop Ser. 2019. 91:99-109. doi:10.1159/000493701. | Mediators/moderators; Intervention/exposure - KQ3
76 | Bailey-Davis, L, Kling, SMR, Cochran, WJ, Hassink, S, Hess, L, Franceschelli Hosterman, J, Lutcher, S, Marini, M, Mowery, J, Paul, IM, Savage, JS. Integrating and coordinating care between the Women, Infants, and Children Program and pediatricians to improve patient-centered preventive care for healthy growth. Transl Behav Med. 2018. 8:944-952. doi:10.1093/tbm/ibx046. | Study participants
77 | Baker, N, Potts, L, Jennings, S, Trevillion, K, Howard, LM. Factors Affecting Infant Feeding Practices Among Women With Severe Mental Illness. Front Glob Womens Health. 2021. 2:624485. doi:10.3389/fgwh.2021.624485. | Study participants
78 | Balkam, JA, Cadwell, K, Fein, SB. Effect of components of a workplace lactation program on breastfeeding duration among employees of a public-sector employer. Matern Child Health J. 2011. 15:677-83. doi:10.1007/s10995-010-0620-9. | Mediators/moderators; Study participants
79 | Ball, H. Supportive practices among hospital staff are strongly linked to chances of breast-feeding. Perspectives on Sexual & Reproductive Health. 2009. 41:191-192. | Study design
80 | Ball, HL, Howel, D, Bryant, A, Best, E, Russell, C, Ward-Platt, M. Bed-sharing by breastfeeding mothers: who bed-shares and what is the relationship with breastfeeding duration?. Acta Paediatr. 2016. 105:628-34. doi:10.1111/apa.13354. | Mediators/moderators; Intervention/exposure - KQ3
81 | Ballou, J, Wiseman, C, Jackson, L, Godfrey, R, Cagle, D. Lactation Skills Workshop: A Collaboration of the City of Dallas WIC and Local Hospitals. J Nutr Educ Behav. 2017. 49:S202-S206.e1. doi:10.1016/j.jneb.2017.05.347. | Study participants
82 | Balyakina, E, Fulda, KG, Franks, SF, Cardarelli, KM, Hinkle, K. Association Between Healthcare Provider Type and Intent to Breastfeed Among Expectant Mothers. Matern Child Health J. 2016. 20:993-1000. doi:10.1007/s10995-015-1884-x. | Outcome
83 | Bandoli, G, Ehrenstein, O, Flores, M, Ritz, B. Breastfeeding and Asthmatic Symptoms in The Offspring of Latinas: The Role of Maternal Nativity. Journal of Immigrant & Minority Health. 2015. 17:1739-1745. doi:10.1007/s10903-015-0158-4. | Intervention/exposure - KQ3; Comparator - KQ2
84 | Banks, E, Killpack, S, Furman, L. Low-income Inner-City Fathers and Breastfeeding-Where’s the Program for Us?. Breastfeeding Medicine. 2013. 8:507-508. doi:10.1089/bfm.2012.0147. | Outcome
85 | Barnett, J, Aguilar, S, Brittner, M, Bonuck, K. Recruiting and retaining low-income, multi-ethnic women into randomized controlled trials: successful strategies and staffing. Contemp Clin Trials. 2012. 33:925-32. doi:10.1016/j.cct.2012.06.005. | Outcome
86 | Barr, JJ, Marugg, L. Impact of Marriage on Birth Outcomes: Pregnancy Risk Assessment Monitoring System, 2012-2014. Linacre Q. 2019. 86:225-230. doi:10.1177/0024363919843019. | Mediators/moderators; Intervention/exposure - KQ3
87 | Barry, AA, Smith, JZ, Deutsch, FM, Perry-Jenkins, M. Fathers’ Involvement in Child Care and Perceptions of Parenting Skill Over the Transition to Parenthood. Journal of Family Issues. 2011. 32:1500-1521. doi:10.1177/0192513X11406229. | Intervention/exposure - KQ3; Independent variable - KQ2
88 | Bartick, M, Barr, AW, Feldman-Winter, L, Guxens, M, Tiemeier, H. The Role of Breastfeeding in Racial and Ethnic Disparities in Sudden Unexpected Infant Death: A Population-Based Study of 13 Million Infants From the United States. Am J Epidemiol. 2022. 191:1190-201. doi:10.1093/aje/kwac050. | Outcome
89 | Bartick, M, Stuebe, A, Shealy, KR, Walker, M, Grummer-Strawn, LM. Closing the Quality Gap: Promoting Evidence-Based Breastfeeding Care in the Hospital. Pediatrics. 2009. 124:E793-E802. doi:10.1542/peds.2009-0430. | Outcome
90 | Bartick, MC, Jegier, BJ, Green, BD, Schwarz, EB, Reinhold, AG, Stuebe, AM. Disparities in Breastfeeding: Impact on Maternal and Child Health Outcomes and Costs. J Pediatr. 2017. 181:49-55.e6. doi:10.1016/j.jpeds.2016.10.028. | Study design
91 | Bartok, CJ, Schaefer, EW, Beiler, JS, Paul, IM. Role of Body Mass Index and Gestational Weight Gain in Breastfeeding Outcomes. Breastfeeding Medicine. 2012. 7:448-456. doi:10.1089/bfm.2011.0127. | Mediators/moderators; Intervention/exposure - KQ3
92 | Bascom, EM, Napolitano, MA. Breastfeeding Duration and Primary Reasons for Breastfeeding Cessation among Women with Postpartum Depressive Symptoms. J Hum Lact. 2016. 32:282-91. doi:10.1177/0890334415619908. | Mediators/moderators; Intervention/exposure - KQ3
93 | Batan, M, Li, R, Scanlon, K. Association of child care providers breastfeeding support with breastfeeding duration at 6 months. Matern Child Health J. 2013. 17:708-13. doi:10.1007/s10995-012-1050-7. | Intervention/exposure - KQ3; Independent variable - KQ2
94 | Battersby, S. Understanding the social and cultural influences on breast-feeding today. J Fam Health Care. 2010. 20:128-31. | Study design
95 | Baumgartner, T, Bhamidipalli, SS, Guise, D, Daggy, J, Parker, CB, Westermann, M, Parry, S, Grobman, WA, Mercer, BM, Simhan, HN, Silver, RM, Wapner, RJ, Saade, GR, Reddy, UM, Haas, DM. Psychosocial and Sociodemographic Contributors to Breastfeeding Intention in First-Time Mothers. Matern Child Health J. 2020. 24:1047-1056. doi:10.1007/s10995-020-02928-0. | Mediators/moderators; Intervention/exposure - KQ3
96 | Beauregard, JL, Hamner, HC, Chen, J, Avila-Rodriguez, W, Elam-Evans, LD, Perrine, CG. Racial Disparities in Breastfeeding Initiation and Duration Among U.S. Infants Born in 2015. MMWR Morb Mortal Wkly Rep. 2019. 68:745-748. doi:10.15585/mmwr.mm6834a3. | Mediators/moderators; Intervention/exposure - KQ3
97 | Belay, B, Allen, J, Williams, N, Dooyema, C, Foltz, J. Promoting women’s health in hospitals: a focus on breastfeeding and lactation support for employees and patients. J Womens Health (Larchmt). 2013. 22:1-4. doi:10.1089/jwh.2012.4040. | Outcome
98 | Benakappa, AD, Shivamurthy, P. Beliefs regarding diet during childhood illness. Indian J Community Med. 2012. 37:20-4. doi:10.4103/0970-0218.94016. | Country; Outcome
99 | Benedett, A, Ferraz, L, Silva, IA. Breastfeeding: a search for comfort. Revista de Pesquisa: Cuidado e Fundamental. 2018. 10:458-464. doi:10.9789/2175-5361.2018.v10i2.458-464. | Country
100 | Benjamin Neelon, SE, Østbye, T, Bennett, GG, Kravitz, RM, Clancy, SM, Stroo, M, Iversen, E, Hoyo, C. Cohort profile for the Nurture Observational Study examining associations of multiple caregivers on infant growth in the Southeastern USA. BMJ Open. 2017. 7:e013939. doi:10.1136/bmjopen-2016-013939. | Outcome
101 | Benjamin Neelon, SE, Stroo, M, Mayhew, M, Maselko, J, Hoyo, C. Correlation between maternal and infant cortisol varies by breastfeeding status. Infant Behav Dev. 2015. 40:252-8. doi:10.1016/j.infbeh.2015.06.005. | Mediators/moderators; Intervention/exposure - KQ3
102 | Bennett, CF, Grassley, JS. A Community Partnership to Support Breastfeeding Mothers of Late Preterm Infants. Nurs Womens Health. 2017. 21:274-282. doi:10.1016/j.nwh.2017.06.004. | Outcome
103 | Bennett, CF, Grassley, JS. Bridging the Gap Between Hospital and Home for Breastfeeding Late Preterm Infants. JOGNN: Journal of Obstetric, Gynecologic & Neonatal Nursing. 2017. 46:S5-S5. doi:10.1016/j.jogn.2017.04.121. | Publication status
104 | Bennett, CJ, Mannel, R. Walking the Medicaid Policy Tightrope Between Long-Acting Reversible Contraception and Lactation. J Hum Lact. 2018. 34:433-437. doi:10.1177/0890334418765940. | Outcome
105 | Bensley, RJ, Hovis, A, Horton, KD, Loyo, JJ, Bensley, KM, Phillips, D, Desmangles, C. Accessibility and preferred use of online Web applications among WIC participants with Internet access. J Nutr Educ Behav. 2014. 46:S87-92. doi:10.1016/j.jneb.2014.02.007. | Outcome
106 | Ben-Zion, H, Volkovich, E, Meiri, G, Tikotzky, L. Mother-Infant Sleep and Maternal Emotional Distress in Solo-Mother and Two-Parent Families. J Pediatr Psychol. 2020. 45:181-193. doi:10.1093/jpepsy/jsz097. | Country
107 | Berger, PK, Lavner, JA, Smith, JJ, Birch, LL. Differences in early risk factors for obesity between African American formula-fed infants and White breastfed controls. Pilot Feasibility Stud. 2017. 3:58. doi:10.1186/s40814-017-0198-8. | Outcome
108 | Bernal, D. The Effect of a Peer Counseling Support Program on Breastfeeding Initiation, Duration and Exclusivity among Low-Income Hispanic Women. Brandman University; 2018. | Publication status
109 | Bernard, JY, Cohen, E, Kramer, MS. Breast feeding initiation rate across Western countries: does religion matter? An ecological study. BMJ Glob Health. 2016. 1:e000151. doi:10.1136/bmjgh-2016-000151. | Mediators/moderators; Intervention/exposure - KQ3
110 | Bernard, JY, Rifas-Shiman, SL, Cohen, E, Lioret, S, de Lauzon-Guillain, B, Charles, MA, Kramer, MS, Oken, E. Maternal religion and breastfeeding intention and practice in the US Project Viva cohort. Birth. 2020. 47:191-201. doi:10.1111/birt.12477. | Mediators/moderators; Intervention/exposure - KQ3
111 | Berry, DC, Hall, EG, Neal, MN, Adatorwovor, R, Schwartz, TA, Stuebe, A. Results of the Optimizing Outcomes in Women with Gestational Diabetes Mellitus and Their Infants, a Cluster Randomized, Controlled Pilot Study: Lessons Learned. J Natl Black Nurses Assoc. 2016. 27:1-10. | Outcome
112 | Bersak, T, Sonchak-Ardan, L. Marginal changes, marginal impacts: The limits of changes to WIC and their ability to influence breastfeeding rates. Children and Youth Services Review. 2021. 126:8. doi:10.1016/j.childyouth.2021.106043. | Mediators/moderators; Study participants
113 | Berthran, CC, Odetola, TD, Abiona, MO. Improving maternal and child health outcomes through active male partner involvement in perinatal care. British Journal of Midwifery. 2021. 29:130-138. doi:10.12968/bjom.2021.29.3.130. | Country
114 | Betts, RC, Johnson, HM, Eglash, A, Mitchell, KB. It’s Not Yeast: Retrospective Cohort Study of Lactating Women with Persistent Nipple and Breast Pain. Breastfeed Med. 2021. 16:318-324. doi:10.1089/bfm.2020.0160. | Outcome
115 | Bich, TH, Long, TK, Hoa, DP. Community-based father education intervention on breastfeeding practice-Results of a quasi-experimental study. Matern Child Nutr. 2019. 15 Suppl 1:e12705. doi:10.1111/mcn.12705. | Country
116 | Biediger-Friedman, L, Silva, M, Crixell, S, Friedman, B, Smith, KS. Intent to Use WIC Smartphone Application to Promote Breastfeeding, Physical Activity, and Healthy Eating in WIC Participants. Journal of Nutrition Education & Behavior. 2015. 47:S55-6. doi:10.1016/j.jneb.2015.04.147. | Publication status
117 | Black, AD. Managing the Breastfeeding Patient in the Emergency Department. Annals of Emergency Medicine. 2020. 75:105-110. doi:10.1016/j.annemergmed.2019.06.015. | Study design
118 | Black, R, McLaughlin, M, Giles, M. Women’s experience of social media breastfeeding support and its impact on extended breastfeeding success: A social cognitive perspective. British Journal of Health Psychology. 2020. 25:754-771. doi:10.1111/bjhp.12451. | Country
119 | Black, RE, Heidkamp, R. Causes of Stunting and Preventive Dietary Interventions in Pregnancy and Early Childhood. Nestle Nutr Inst Workshop Ser. 2018. 89:105-113. doi:10.1159/000486496. | Study design
120 | Blackman, KCA, Slama, DS, Pickering, TA, Russell, A, Valentine, W, Merchant, MA, Saetermoe, C. Evaluation of a breastfeeding promotion film among a racially minoritized sample. BMC Pregnancy Childbirth. 2022. 22:262. doi:10.1186/s12884-022-04607-0. | Outcome
121 | Blackwell, D, Morrell, E. Community Perspectives During a Lead Contaminated Drinking Water Crisis: Lessons for Lactation and Other Health Providers. J Hum Lact. 2021. 37:331-342. doi:10.1177/0890334420933134. | Intervention/exposure - KQ3; Outcome
122 | Blanco, CE. Promotoras: A Culturally Sensitive Intervention for Hispanic Breastfeeding Women. JOGNN: Journal of Obstetric, Gynecologic & Neonatal Nursing. 2011. 40:S19-S19. doi:10.1111/j.1552-6909.2011.01242_25.x. | Publication status
123 | Blue, CM, Arnett, MC, Ephrem, H, Lunos, S, Ruoqiong, C, Jones, R. Using motivational interviewing to reduce parental risk related behaviors for early childhood caries: a pilot study. BMC Oral Health. 2020. 20:1-8. doi:10.1186/s12903-020-1052-6. | Outcome
124 | Bogaerts, AF, Van den Bergh, BR, Witters, I, Devlieger, R. Anxiety during early pregnancy predicts postpartum weight retention in obese mothers. Obesity (Silver Spring). 2013. 21:1942-9. doi:10.1002/oby.20352. | Country
125 | Bogen, DL, Hanusa, BH, Moses-Kolko, E, Wisner, KL. Are maternal depression or symptom severity associated with breastfeeding intention or outcomes?. J Clin Psychiatry. 2010. 71:1069-78. doi:10.4088/JCP.09m05383blu. | Intervention/exposure - KQ3
126 | Bolton, TA, Chow, T, Benton, PA, Olson, BH. Characteristics associated with longer breastfeeding duration: an analysis of a peer counseling support program. J Hum Lact. 2009. 25:18-27. doi:10.1177/0890334408325985. | Mediators/moderators; Study participants
127 | Bonuck, K, Avraham, SB, Lo, Y, Kahn, R, Hyden, C. Bottle-weaning intervention and toddler overweight. J Pediatr. 2014. 164:306-12.e1-2. doi:10.1016/j.jpeds.2013.09.029. | Mediators/moderators; Intervention/exposure - KQ3
128 | Borger, C, Weinfield, NS, Paolicelli, C, Sun, B, May, L. Prenatal and Postnatal Experiences Predict Breastfeeding Patterns in the WIC Infant and Toddler Feeding Practices Study-2. Breastfeed Med. 2021. 16:869-877. doi:10.1089/bfm.2021.0054. | Mediators/moderators; Intervention/exposure - KQ3
129 | Bosnjak, AP, Grguric, J, Stanojevic, M, Sonicki, Z. Influence of sociodemographic and psychosocial characteristics on breastfeeding duration of mothers attending breastfeeding support groups. J Perinat Med. 2009. 37:185-92. doi:10.1515/jpm.2009.025. | Country
130 | Boundy, EO, Perrine, CG, Nelson, JM, Hamner, HC. Disparities in Hospital-Reported Breast Milk Use in Neonatal Intensive Care Units - United States, 2015. MMWR Morb Mortal Wkly Rep. 2017. 66:1313-1317. doi:10.15585/mmwr.mm6648a1. | Mediators/moderators; Intervention/exposure - KQ3; Outcome
131 | Bourne, DA, Chen, W, Schilling, BK, Littleton, EB, Washington, KM, De La Cruz, C. The Impact of Plastic Surgery Training on Family Planning and Prenatal Health. Plast Reconstr Surg. 2019. 144:1227-1236. doi:10.1097/prs.0000000000006100. | Study participants
132 | Boutrid, N, Rahmoune, H, Boutrid, H. Breastfeeding for Primary Prevention of Stroke. Journal of the National Medical Association. 2019. 111:688-690. doi:10.1016/j.jnma.2019.06.005. | Outcome; Study design
133 | Bovbjerg, ML, Hill, JA, Uphoff, AE, Rosenberg, KD. Women Who Bedshare More Frequently at 14 Weeks Postpartum Subsequently Report Longer Durations of Breastfeeding. J Midwifery Womens Health. 2018. 63:418-424. doi:10.1111/jmwh.12753. | Mediators/moderators; Intervention/exposure - KQ3
134 | Bowman, KG, Ryberg, JW, Becker, H. Examining the relationship between a childhood history of sexual abuse and later dissociation, breast-feeding practices, and parenting anxiety. J Interpers Violence. 2009. 24:1304-17. doi:10.1177/0886260508322196. | Intervention/exposure - KQ3; Comparator
135 | Boyd, L, Hackett, M, Magid, E. Health departments helping hospitals: a New York City breastfeeding case study. Breastfeed Med. 2011. 6:267-9. doi:10.1089/bfm.2011.0078. | Mediators/moderators; Comparator - KQ3
136 | Brand, Elizabeth, Kothari, Catherine, Stark, Mary Ann. Factors Related to Breastfeeding Discontinuation Between Hospital Discharge and 2 Weeks Postpartum. Journal of Perinatal Education. 2011. 20:36-44. doi:10.1891/1058-1243.20.1.36. | Mediators/moderators; Intervention/exposure - KQ3
137 | Brandão Lopes, B, Chaves Lopes, AF, Giffoni Soares, D, Dayana Dodou, H, Moura Barbosa Castro, RC, Batista Oriá, MO. Assessment of maternal self-efficacy in breastfeeding in the immediate puerperium. Rev Rene. 2017. 18:818-824. doi:10.15253/2175-6783.2017000600016. | Country
138 | Bream, E, Li, H, Furman, L. The Effect of Breast Pump Use on Exclusive Breastfeeding at 2 Months Postpartum in an Inner-City Population. Breastfeed Med. 2017. 12:149-155. doi:10.1089/bfm.2016.0160. | Mediators/moderators; Intervention/exposure - KQ3
139 | Brennan, RA, Callaway, S. Innovations in Practice: Supporting the Breastfeeding Dyad in Labor & Delivery. JOGNN: Journal of Obstetric, Gynecologic & Neonatal Nursing. 2014. 43:S62-S63. doi:10.1111/1552-6909.12347. | Publication status
140 | Brenneman, A, Price, KM. Couplet Care: The Magic Within. JOGNN: Journal of Obstetric, Gynecologic & Neonatal Nursing. 2014. 43:S28-S28. doi:10.1111/1552-6909.12363. | Publication status
141 | Bresnahan, M, Goldbort, J, Zhuang, J, Bogdan-Lovis, E, Yan, X. Promoting Sustained and Exclusive Breastfeeding among Chinese American Pregnant Women. J Health Commun. 2020. 25:576-583. doi:10.1080/10810730.2020.1822471. | Outcome
142 | Bresnahan, M, Zhuang, J, Anderson, J, Zhu, Y, Nelson, J, Yan, X. The “pumpgate” incident: Stigma against lactating mothers in the U.S. workplace. Women Health. 2018. 58:451-465. doi:10.1080/03630242.2017.1306608. | Intervention/exposure - KQ3; Independent variable - KQ2; Study participants
143 | Bresnahan, M, Zhuang, J, Goldbort, J, Bogdan-Lovis, E, Park, SY, Hitt, R. Made to Feel Like Less of a Woman: The Experience of Stigma for Mothers Who Do Not Breastfeed. Breastfeed Med. 2020. 15:35-40. doi:10.1089/bfm.2019.0171. | Mediators/moderators; Intervention/exposure - KQ3
144 | Briere, CE, McGrath, JM, Cong, X, Brownell, E, Cusson, R. Direct-Breastfeeding Premature Infants in the Neonatal Intensive Care Unit. J Hum Lact. 2015. 31:386-92. doi:10.1177/0890334415581798. | Mediators/moderators; Intervention/exposure - KQ3
145 | Brockman, V. Implementing the Mother-Baby Model of Nursing Care Using Models and Quality Improvement Tools. Nurs Womens Health. 2015. 19:490-503. doi:10.1111/1751-486x.12245. | Study participants
146 | Brockway, M, Benzies, KM, Carr, E, Aziz, K. Does breastfeeding self-efficacy theory apply to mothers of moderate and late preterm infants? A qualitative exploration. J Clin Nurs. 2020. 29:2872-2885. doi:10.1111/jocn.15304. | Country
147 | Brodribb, WE. Breastfeeding Women in the Paid Workforce. Breastfeed Med. 2015. 10:349. doi:10.1089/bfm.2015.29000. | Study design
148 | Broussard, DL, Sappenfield, WM, Goodman, DA. The Black and White of infant back sleeping and infant bed sharing in Florida, 2004-2005. Matern Child Health J. 2012. 16:713-24. doi:10.1007/s10995-011-0768-y. | Outcome
149 | Brown, A, Rance, J, Bennett, P. Understanding the relationship between breastfeeding and postnatal depression: the role of pain and physical difficulties. J Adv Nurs. 2016. 72:273-82. doi:10.1111/jan.12832. | Mediators/moderators; Intervention/exposure - KQ3
150 | Brown, A, Rance, J, Warren, L. Body image concerns during pregnancy are associated with a shorter breast feeding duration. Midwifery. 2015. 31:80-89. doi:10.1016/j.midw.2014.06.003. | Country
151 | Brown, A, Raynor, P, Lee, M. Maternal control of child-feeding during breast and formula feeding in the first 6 months post-partum. Journal of Human Nutrition & Dietetics. 2011. 24:177-186. doi:10.1111/j.1365-277X.2010.01145.x. | Country
152 | Brown, A, Raynor, P, Lee, M. Young mothers who choose to breast feed: the importance of being part of a supportive breast-feeding community. Midwifery. 2011. 27:53-59. doi:10.1016/j.midw.2009.09.004. | Country
153 | Brown, A. Maternal restraint and external eating behaviour are associated with formula use or shorter breastfeeding duration. Appetite. 2014. 76:30-35. doi:10.1016/j.appet.2013.12.022. | Country
154 | Brown, A. Maternal trait personality and breastfeeding duration: the importance of confidence and social support. Journal of Advanced Nursing. 2014. 70:587-598. doi:10.1111/jan.12219. | Country
155 | Brown, C, Davis, KE, Habiba, N, Massey-Stokes, M, Warren, C. Parent preferences for text messages containing infant feeding advice. Mhealth. 2020. 6:9. doi:10.21037/mhealth.2019.11.03. | Independent variable - KQ2; Outcome
156 | Brown, H. Racial Health Disparities And Fetal Programming. Contemporary OB/GYN. 2013. 58:44-44. | Outcome
157 | Brown, LL, Talker, R, Stoddard, GJ, Clayton, J, Millar, MM, Jo, Y, Bardsley, T, Stipelman, CH. Breastfeeding Attitudes and Practices in a Rural Utah Navajo Community. Matern Child Health J. 2022. 26:397-406. doi:10.1007/s10995-021-03247-8. | Mediators/moderators; Intervention/exposure - KQ3
158 | Brown, S, Brage Hudson, D, Campbell-Grossman, C, Yates, BC. Health promotion text blasts for minority adolescent mothers. MCN Am J Matern Child Nurs. 2014. 39:357-62. doi:10.1097/nmc.0000000000000081. | Outcome
159 | Browne, D. Changing the Culture of Breastfeeding Education to Improve Health Outcomes. Breastfeed Med. 2018. 13:541-543. doi:10.1089/bfm.2018.0129. | Study design
160 | Brownell, EA, Fernandez, ID, Fisher, SG, Howard, CR, Ternullo, SR, Lawrence, RA, Duckett, JW, Dozier, AM. The effect of immediate postpartum depot medroxyprogesterone on early breastfeeding cessation. Contraception. 2013. 87:836-43. doi:10.1016/j.contraception.2012.08.045. | Mediators/moderators; Study participants
161 | Brownell, EA, Lussier, MM, Hagadorn, JI, McGrath, JM, Marinelli, KA, Herson, VC. Independent predictors of human milk receipt at neonatal intensive care unit discharge. Am J Perinatol. 2014. 31:891-8. doi:10.1055/s-0033-1363500. | Mediators/moderators; Intervention/exposure - KQ3
162 | Bruney, Talitha, Campbell, Deborah, Iyare, Abieyuwa. Achieving Baby-Friendly Designation at a Large Metropolitan Center. American Journal of Perinatology. 2020. 37:430-435. doi:10.1055/s-0039-1681056. | Independent variable - KQ2; Study participants
163 | Bryant, AG, Lyerly, AD, DeVane-Johnson, S, Kistler, CE, Stuebe, AM. Hormonal contraception, breastfeeding and bedside advocacy: the case for patient-centered care. Contraception. 2019. 99:73-76. doi:10.1016/j.contraception.2018.10.011. | Study design
164 | Brzezinski, Lisa, Mimm, Nancy, Porter, Sallie. Pediatric Nurse Practitioner Barriers to Supporting Breastfeeding by Mothers and Infants. Journal of Perinatal Education. 2018. 27:207-219. doi:10.1891/1058-1243.27.4.207. | Study participants
165 | Buck, CO, Gjelsvik, A, Vivier, PM, Monteiro, K, Amanullah, S. Prenatal Exposure to Stressful Life Events and Infant Breastfeeding. Breastfeed Med. 2018. 13:426-432. doi:10.1089/bfm.2017.0200. | Mediators/moderators; Intervention/exposure - KQ3
166 | Buckles, K, Kolka, S. Prenatal investments, breastfeeding, and birth order. Soc Sci Med. 2014. 118:66-70. doi:10.1016/j.socscimed.2014.07.055. | Intervention/exposure - KQ3; Independent variable - KQ2
167 | Bullinger, LR, Gurley-Calvez, T. WIC PARTICIPATION AND MATERNAL BEHAVIOR: BREASTFEEDING AND WORK LEAVE. Contemporary Economic Policy. 2016. 34:158-172. doi:10.1111/coep.12123. | Mediators/moderators; Study participants
168 | Bunik, M, Krebs, NF, Beaty, B, McClatchey, M, Olds, DL. Breastfeeding and WIC enrollment in the Nurse Family Partnership Program. Breastfeed Med. 2009. 4:145-9. doi:10.1089/bfm.2008.0140. | Mediators/moderators; Intervention/exposure - KQ3
169 | Bunik, M, Shobe, P, O’Connor, ME, Beaty, B, Langendoerfer, S, Crane, L, Kempe, A. Are 2 weeks of daily breastfeeding support insufficient to overcome the influences of formula?. Acad Pediatr. 2010. 10:21-8. doi:10.1016/j.acap.2009.09.014. | Independent variable - KQ2; Study participants
170 | Burdette, AM. Neighborhood context and breastfeeding behaviors among urban mothers. J Hum Lact. 2013. 29:597-604. doi:10.1177/0890334413495110. | Mediators/moderators; Intervention/exposure - KQ3
171 | Burdette, AM, Pilkauskas, NV. Maternal Religious Involvement and Breastfeeding Initiation and Duration. American Journal of Public Health. 2012. 102:1865-1868. doi:10.2105/AJPH.2012.300737. | Intervention/exposure - KQ3; Independent variable - KQ2
172 | Burnham, L, Matlak, S, Makrigiorgos, G, Braun, N, Knapp, BP, Merewood, A. Breastfeeding and coffee consumption in children younger than 2 years in Boston, Massachusetts, USA. J Hum Lact. 2015. 31:267-72. doi:10.1177/0890334415570971. | Outcome
173 | Burton, A, Taylor, J, Swain, S, Heyes, J, Cust, F, Dean, S. A qualitative exploration of mixed feeding intentions in first-time mothers. British Journal of Midwifery. 2022. 30:20-29. doi:10.12968/bjom.2022.30.1.20. | Country
174 | Busch, DW. Clinical Management of the Breast-Feeding Mother-Infant Dyad in Recovery From Opioid Dependence. Journal of Addictions Nursing. 2016. 27:68-77. doi:10.1097/JAN.0000000000000117. | Study design
175 | Bushaw, A, Lutenbacher, M, Karp, S, Dietrich, M, Graf, M. Infant feeding beliefs and practices: Effects of maternal personal characteristics. Journal for Specialists in Pediatric Nursing. 2020. 25:1-8. doi:10.1111/jspn.12294. | Independent variable - KQ2; Outcome
176 | Buultjens, Melissa, Murphy, Gregory, Milgrom, Jeannette, Taket, Ann, Poinen, Darren. Supporting the transition to parenthood: Development of a group health-promoting programme. British Journal of Midwifery. 2018. 26:387-397. doi:10.12968/bjom.2018.26.6.387. | Country
177 | Byerly, T, Buckman, C, Tumin, D, Bear, K. Prematurity and breastfeeding initiation: A sibling analysis. Acta Paediatr. 2020. 109:2586-2591. doi:10.1111/apa.15290. | Intervention/exposure - KQ3; Independent variable - KQ2
178 | Byrne, ML, Schwartz, OS, Simmons, JG, Sheeber, L, Whittle, S, Allen, NB. Duration of Breastfeeding and Subsequent Adolescent Obesity: Effects of Maternal Behavior and Socioeconomic Status. J Adolesc Health. 2018. 62:471-479. doi:10.1016/j.jadohealth.2017.10.019. | Outcome
179 | Byrom, A. Feeding guilt. Pract Midwife. 2013. 16:18, 20, 22-3. | Independent variable - KQ2; Study participants
180 | Cadwell, K, Brimdyr, K, Phillips, R. Mapping, Measuring, and Analyzing the Process of Skin-to-Skin Contact and Early Breastfeeding in the First Hour After Birth. Breastfeeding Medicine. 2018. 13:485-492. doi:10.1089/bfm.2018.0048. | Outcome
181 | Cahill, JM, Freeland-Graves, JH, Shah, BS, Lu, H, Klohe-Lehman, DM. Development and validation of the eating stimulus index in low-income, minority women in early postpartum. J Am Diet Assoc. 2009. 109:1593-8. doi:10.1016/j.jada.2009.06.364. | Outcome
182 | Camel, SP, Heathman, L, Douglas, CC. A Comparison of Breastfeeding Exposure, Attitude, and Knowledge Between Collegiate African American and White Males with no Biological Children. Matern Child Health J. 2020. 24:875-884. doi:10.1007/s10995-020-02934-2. | Outcome
183 | Cameron, B, Javanparast, S, Labbok, M, Scheckter, R, McIntyre, E. Breastfeeding support in child care: an international comparison of findings from Australia and the United States. Breastfeeding Medicine. 2012. 7:163-166. doi:10.1089/bfm.2011.0032. | Intervention/exposure - KQ3; Independent variable - KQ2
184 | Cândido, FG, Freitas, BAC, Soares, RCS, Bittencourt, JM, Ribeiro, DN, Morais, DC, Niquine, CF, Ribeiro, SAV, Araújo, RMA, Zucchetto, BR, Carvalho, TC, Rezende, IC. Breastfeeding versus free distribution of infant formulas by the Public Health System. Einstein (Sao Paulo). 2021. 19:eAO6451. doi:10.31744/einstein_journal/2021AO6451. | Country
185 | Cantu, RM, Gowen, MS, Tang, X, Mitchell, K. Barriers to Breastfeeding in Female Physicians. Breastfeed Med. 2018. 13:341-345. doi:10.1089/bfm.2018.0022. | Independent variable - KQ2; Study participants
186 | Carlsen, SM, Jacobsen, G, Vanky, E. Mid-pregnancy androgen levels are negatively associated with breastfeeding. Acta Obstet Gynecol Scand. 2010. 89:87-94. doi:10.3109/00016340903318006. | Country
187 | Carr, A. Breastfeeding and the WIC program. Breastfeed Med. 2009. 4 Suppl 1:S57-8. doi:10.1089/bfm.2009.0036. | Study design
188 | Carroll, GJ, Buccini, GS, Pérez-Escamilla, R. Perspective: What Will It Cost to Scale-up Breastfeeding Programs? A Comparison of Current Global Costing Methodologies. Adv Nutr. 2018. 9:572-580. doi:10.1093/advances/nmy041. | Study design
189 | Cartagena, D, Ameringer, SW, McGrath, JM, Masho, SW, Jallo, N, Myers, BJ. Factors contributing to infant overfeeding in low-income immigrant Latina mothers. Appl Nurs Res. 2015. 28:316-21. doi:10.1016/j.apnr.2015.03.007. | Intervention/exposure - KQ3; Comparator - KQ2
190 | Cartagena, D, McGrath, JM, Masho, SW. Differences in modifiable feeding factors by overweight status in Latino infants. Appl Nurs Res. 2016. 30:210-5. doi:10.1016/j.apnr.2015.09.005. | Mediators/moderators; Intervention/exposure - KQ3; Outcome
191 | Cartagena, DC. Factors contributing to infant feeding practices with Latina mothers. Virginia Commonwealth University; 2014. | Publication status
192 | Cartagena, DC. Factors Contributing to Infant Overfeeding in Low-Income Immigrant Hispanic Mothers. JOGNN: Journal of Obstetric, Gynecologic & Neonatal Nursing. 2015. 44:S61-S61. doi:10.1111/1552-6909.12632. | Publication status
193 | Carter, SK, Anthony, AK. Good, Bad, and Extraordinary Mothers: Infant Feeding and Mothering in African American Mothers’ Breastfeeding Narratives. Sociology of Race and Ethnicity. 2015. 1:517-531. doi:10.1177/2332649215581664. | Outcome
194 | Casavant, SG, McGrath, JM, Burke, G, Briere, CE. Caregiving Factors Affecting Breastfeeding Duration Within a Neonatal Intensive Care Unit. Adv Neonatal Care. 2015. 15:421-8. doi:10.1097/anc.0000000000000234. | Mediators/moderators; Intervention/exposure - KQ3
195 | Cayir, E, Felder, TM, Nkwonta, CA, Jackson, JR, Dawson, R. Discovering New Connections: Insights From Individual and Collective Reflexivity in a Mixed Methods Study. International Journal of Qualitative Methods. 2022. 21:14. doi:10.1177/16094069221105707. | Outcome; Study participants
196 | Chamblin, C. Breastfeeding Support: A National Campaign. Illinois Nurse. 2012. 8:9-11. | Study design
197 | Chang, YH, Valliant, M, Bomba, AK. Gender differences in knowledge and attitude regarding breastfeeding. International Journal of Consumer Studies. 2012. 36:342-351. doi:10.1111/j.1470-6431.2010.00994.x. | Outcome
198 | Chapman, DJ, Pérez-Escamilla, R. Acculturative type is associated with breastfeeding duration among low-income Latinas. Matern Child Nutr. 2013. 9:188-98. doi:10.1111/j.1740-8709.2011.00344.x. | Mediators/moderators; Intervention/exposure - KQ3
199 | Chapman, DJ. Lessons learned from African American women who breastfeed. J Hum Lact. 2015. 31:15-6. doi:10.1177/0890334414560731. | Study design
200 | Charkazi, A, Miraeiz, SZ, Razzaghnejad, A, Shahnazi, H, Hasanzadeh, A, Badleh, MT. Breastfeeding status during the first two years of infants’ life and its risk factors based on BASNEF model structures in Isfahan. J Educ Health Promot. 2013. 2:9. doi:10.4103/2277-9531.107938. | Country
201 | Chastain, W, Lipke, J. Perinatal Education in a Community Setting. JOGNN: Journal of Obstetric, Gynecologic & Neonatal Nursing. 2014. 43:S26-S26. doi:10.1111/1552-6909.12399. | Publication status
202 | Chen, C, Xue, H, Zhang, Q. Data on breastfeeding and state policies in the United States. Data Brief. 2021. 37:107210. doi:10.1016/j.dib.2021.107210. | Outcome
203 | Chen, MJ, Hsia, JK, Hou, MY, Wilson, MD, Creinin, MD. Comparing Postpartum Visit Attendance with a Scheduled 2- to 3-Week or 6-Week Visit after Delivery. Am J Perinatol. 2019. 36:936-942. doi:10.1055/s-0038-1675623. | Mediators/moderators; Study participants
204 | Chen, PG, Johnson, LW, Rosenthal, MS. Sources of education about breastfeeding and breast pump use: what effect do they have on breastfeeding duration? An analysis of the Infant Feeding Practices Survey II. Matern Child Health J. 2012. 16:1421-30. doi:10.1007/s10995-011-0908-4. | Mediators/moderators; Study participants
205 | Cheng, D, Schwarz, EB, Douglas, E, Horon, I. Unintended pregnancy and associated maternal preconception, prenatal and postpartum behaviors. Contraception. 2009. 79:194-8. doi:10.1016/j.contraception.2008.09.009. | Intervention/exposure - KQ3; Independent variable - KQ2
206 | Chertok, IR, Luo, J, Culp, S, Mullett, M. Intent to breastfeed: a population-based perspective. Breastfeed Med. 2011. 6:125-9. doi:10.1089/bfm.2010.0013. | Outcome
207 | Chertok, IRA, Hoover, ML. Breastfeeding legislation in states with relatively low breastfeeding rates compared to breastfeeding legislation of other states [corrected] [published erratum appears in J NURS LAW 2009;13(3):1p]. Journal of Nursing Law. 2009. 13:45-53. doi:10.1891/1073-7472.13.2.45. | Independent variable - KQ2; Study participants
208 | Chetwynd, EM, Facelli, V. Lactation Support for LGBTQIA+ Families. J Hum Lact. 2019. 35:244-247. doi:10.1177/0890334419831269. | Mediators/moderators; Comparator - KQ3
209 | Chetwynd, EM, Stuebe, AM, Rosenberg, L, Troester, MA, Palmer, JR. Prepregnancy Diabetes and Breastfeeding Cessation Among Black Women in the United States. Breastfeed Med. 2019. 14:249-255. doi:10.1089/bfm.2018.0074. | Mediators/moderators; Intervention/exposure - KQ3
210 | Cheyney, M, Bovbjerg, M, Everson, C, Gordon, W, Hannibal, D, Vedam, S. Outcomes of Care for 16,924 Planned Home Births in the United States: The Midwives Alliance of North America Statistics Project, 2004 to 2009. Journal of Midwifery & Women’s Health. 2014. 59:17-27. doi:10.1111/jmwh.12172. | Intervention/exposure - KQ3; Independent variable - KQ2
211 | Cheyney, M, Henning, M, Horan, H, Bovbjerg, ML, Ferguson, M. From Policy to Practice: Women’s Experiences of Breastfeeding-Friendly Worksites, Part 1. Clinical Lactation. 2019. 10:104-112. doi:10.1891/2158-0782.10.3.104. | Independent variable - KQ2; Study participants
212 | Chezem, JC. Breastfeeding attitudes among couples planning exclusive breastfeeding or mixed feeding. Breastfeed Med. 2012. 7:155-62. doi:10.1089/bfm.2011.0024. | Outcome
213 | Chiang, KV, Sharma, AJ, Nelson, JM, Olson, CK, Perrine, CG. Receipt of Breast Milk by Gestational Age - United States, 2017. MMWR Morb Mortal Wkly Rep. 2019. 68:489-493. doi:10.15585/mmwr.mm6822a1. | Study design
214 | Chiao, C, Kaye, E, Scott, T, Hayes, C, Garcia, RI. Breastfeeding and Early Childhood Caries: Findings from the National Health and Nutrition Examination Survey, 2011 to 2018. Pediatr Dent. 2021. 43:276-281. | Outcome
215 | Chin, NP, Cuculick, J, Starr, M, Panko, T, Widanka, H, Dozier, A. Deaf mothers and breastfeeding: do unique features of deaf culture and language support breastfeeding success?. J Hum Lact. 2013. 29:564-71. doi:10.1177/0890334413476921. | Study participants
216 | Christopher, GC, Krell, JK. Changing the breastfeeding conversation and our culture. Breastfeeding Medicine. 2014. 9:53-55. doi:10.1089/bfm.2014.9994. | Independent variable - KQ2; Outcome; Study participants
217 | Claesson, IM, Myrgård, M, Wallberg, M, Blomberg, M. The Association Between Covariates, with Emphasis on Maternal Body Mass Index, and Duration of Exclusive and Total Breastfeeding. Breastfeed Med. 2020. 15:622-629. doi:10.1089/bfm.2019.0138. | Country
218 | Clark, A, Baker, SS, McGirr, K, Harris, M. Breastfeeding Peer Support Program Increases Breastfeeding Duration Rates Among Middle- to High-Income Women. Breastfeed Med. 2018. 13:112-115. doi:10.1089/bfm.2017.0021. | Independent variable - KQ2; Study participants
219 | Clark, C, Price, K. Exploring the role of social support in understanding barriers to breastfeeding practices for adolescent mothers in Western North Carolina: A preliminary study. International Public Health Journal. 2018. 10:333-342. | Study participants
220 | Clinical digest. Adequate maternity leave important for breastfeeding success. Nursing Standard. 2009. 23:15-15. | Study design
221 | Cloutier, MM, Wiley, J, Wang, Z, Grant, A, Gorin, AA. The Early Childhood Obesity Prevention Program (ECHO): an ecologically-based intervention delivered by home visitors for newborns and their mothers. BMC Public Health. 2015. 15:584. doi:10.1186/s12889-015-1897-9. | Outcome; Other (Protocol)
222 | Coburn, SS, Luecken, LJ, Rystad, IA, Lin, B, Crnic, KA, Gonzales, NA. Prenatal Maternal Depressive Symptoms Predict Early Infant Health Concerns. Matern Child Health J. 2018. 22:786-793. doi:10.1007/s10995-018-2448-7. | Intervention/exposure - KQ3; Outcome
223 | Coduti, N, Gregoire, M, Sowa, D, Diakakis, GM, Chen, YM. Characteristics of Exclusively Breastfeeding Mothers. Topics in Clinical Nutrition. 2015. 30:174-183. doi:10.1097/tin.0000000000000033. | Mediators/moderators; Intervention/exposure - KQ3
224 | Cohen, M, Botz, C. Lactation in quarantine: The (in)visibility of human milk feeding during the COVID-19 pandemic in the United States. Int Breastfeed J. 2022. 17:22. doi:10.1186/s13006-022-00451-2. | Independent variable - KQ2; Study participants
225 | Cohen, SS, Larson, CO, Matthews, CE, Buchowski, MS, Signorello, LB, Hargreaves, MK, Blot, WJ. Parity and breastfeeding in relation to obesity among black and white women in the southern community cohort study. J Womens Health (Larchmt). 2009. 18:1323-32. doi:10.1089/jwh.2008.1181. | Outcome
226 | Colaizy, TT, Saftlas, AF, Morriss, FH, Colaizy, TarahT, Saftlas, AudreyF, Morriss, FrankH, Jr. Maternal intention to breast-feed and breast-feeding outcomes in term and preterm infants: Pregnancy Risk Assessment Monitoring System (PRAMS), 2000-2003. Public Health Nutrition. 2012. 15:702-710. doi:10.1017/S1368980011002229. | Mediators/moderators; Intervention/exposure - KQ3
227 | Colchamiro, R, Edwards, RA, Nordstrom, C, Eshelman, J, Ghiringhelli, K, Forgit, J, Tolan, E, Mainello, K, Foley, J. Mobilizing Community Resources to Enhance Postdischarge Support for Breastfeeding in Massachusetts (USA): Results of a Catalyst Grant Approach. J Hum Lact. 2015. 31:631-40. doi:10.1177/0890334415597680. | Outcome
228 | Colling, K, Ward, L, Beck, A, Nommsen-Rivers, LA. Contribution of Maternal Obesity to Medically Indicated and Elective Formula Supplementation in a Baby-Friendly Hospital. Breastfeed Med. 2019. 14:236-242. doi:10.1089/bfm.2018.0185. | Mediators/moderators; Intervention/exposure - KQ3
229 | Collins, BN, DiSantis, KI, Nair, US. Longer previous smoking abstinence relates to successful breastfeeding initiation among underserved smokers. Breastfeed Med. 2011. 6:385-91. doi:10.1089/bfm.2010.0076. | Mediators/moderators; Intervention/exposure - KQ3
230 | Condon, L, Rhodes, C, Warren, S, Withall, J, Tapp, A. ‘But is it a normal thing?’ Teenage mothers’ experiences of breastfeeding promotion and support. Health Education Journal. 2013. 72:156-162. doi:10.1177/0017896912437295. | Country
231 | Conner, M, McEachan, R, Jackson, C, McMillan, B, Woolridge, M, Lawton, R. Moderating effect of socioeconomic status on the relationship between health cognitions and behaviors. Ann Behav Med. 2013. 46:19-30. doi:10.1007/s12160-013-9481-y. | Mediators/moderators; Intervention/exposure - KQ3; Country
232 | Cooklin, AR, Rowe, HJ, Fisher, JR. Paid parental leave supports breastfeeding and mother-infant relationship: a prospective investigation of maternal postpartum employment. Aust N Z J Public Health. 2012. 36:249-56. doi:10.1111/j.1753-6405.2012.00846.x. | Country
233 | Cordero, L, Gabbe, SG, Landon, MB, Nankervis, CA. Breastfeeding initiation in women with gestational diabetes mellitus. J Neonatal Perinatal Med. 2013. 6:303-10. doi:10.3233/npm-1372513. | Mediators/moderators; Intervention/exposure - KQ3
234 | Cordero, L, Paetow, P, Landon, MB, Nankervis, CA. Neonatal outcomes of macrosomic infants of diabetic and non-diabetic mothers. J Neonatal Perinatal Med. 2015. 8:105-12. doi:10.3233/npm-15814102. | Mediators/moderators; Intervention/exposure - KQ3
235 | Cordero, L, Thung, S, Landon, MB, Nankervis, CA. Breast-feeding initiation in women with pregestational diabetes mellitus. Clin Pediatr (Phila). 2014. 53:18-25. doi:10.1177/0009922813496455. | Mediators/moderators; Intervention/exposure - KQ3
236 | Cordero, L, Valentine, CJ, Samuels, P, Giannone, PJ, Nankervis, CA. Breastfeeding in women with severe preeclampsia. Breastfeed Med. 2012. 7:457-63. doi:10.1089/bfm.2012.0019. | Mediators/moderators; Intervention/exposure - KQ3
237 | Cornell, E, Lerer, T, Hagadorn, JI, Chapman, DJ, Lussier, M, Brownell, E. A well-baby peer counseling program is not associated with human milk receipt in the NICU. Journal of Perinatology. 2016. 36:758-762. doi:10.1038/jp.2016.75. | Mediators/moderators; Study participants
238 | Cortelo, FM, Marba, STM, Cortellazzi, KL, Ambrosano, GMB, Guerra, LM, Almeida, ACG, Tomar, SL, Silva, MRD, Possobon, RF. Women’s sense of coherence and its association with early weaning. J Pediatr (Rio J). 2018. 94:624-629. doi:10.1016/j.jped.2017.08.007. | Country
239 | Cota-Robles, S, Pedersen, L, LeCroy, CW. Challenges to Breastfeeding Initiation and Duration for Teen Mothers. MCN Am J Matern Child Nurs. 2017. 42:173-178. doi:10.1097/nmc.0000000000000327. | Mediators/moderators; Intervention/exposure - KQ3
240 | Cox, JE. The Lived Experience of Childbirth among 21st Century Cuban Women In a Florida Hospital. Catholic University of America; 2011. | Publication status
241 | Craighead, DV, Elswick, RK, Jr. The influence of early-term birth on NICU admission, length of stay, and breastfeeding initiation and duration. J Obstet Gynecol Neonatal Nurs. 2014. 43:409-21. doi:10.1111/1552-6909.12472. | Mediators/moderators; Intervention/exposure - KQ3
242 | Cremonese, L, Antunes Wilhelm, L, Alende Prates, L, Oliveira, G, Nunes Barreto, C, Ressel, LB. Breastfeeding Process In Adolescence: Experiences Recollected By Women. Journal of Nursing UFPE / Revista de Enfermagem UFPE. 2016. 10:3284-3292. doi:10.5205/reuol.9571-83638-1-SM1009201613. | Country
243 | Crenshaw, JT, Budin, WD. Hospital Care Practices Associated With Exclusive Breastfeeding 3 and 6 Months After Discharge: A Multisite Study. Journal of Perinatal Education. 2020. 29:143-151. doi:10.1891/J-PE-D-19-00033. | Independent variable - KQ2; Study participants
244 | Crenshaw, JT, Cadwell, K, Brimdyr, K, Widström, AM, Svensson, K, Champion, JD, Gilder, RE, Winslow, EH. Use of a video-ethnographic intervention (PRECESS Immersion Method) to improve skin-to-skin care and breastfeeding rates. Breastfeeding Medicine. 2012. 7:69-78. | Independent variable - KQ2; Study participants
245 | Crespo-Fierro, Michele. Supporting Breast-feeding When a Woman Is Homeless. International Journal of Nursing Terminologies & Classifications. 2011. 22:103-107. doi:10.1111/j.1744-618X.2010.01170.x. | Intervention/exposure - KQ3; Outcome
246 | Crestani, AH, Souza, AP, Beltrami, L, Moraes, AB. Analysis of the association among types of breastfeeding, presence of child development risk, socioeconomic and obstetric variables. J Soc Bras Fonoaudiol. 2012. 24:205-10. doi:10.1590/s2179-64912012000300004. | Country
247 | Crippa, BL, Colombo, L, Morniroli, D, Consonni, D, Bettinelli, ME, Spreafico, I, Vercesi, G, Sannino, P, Mauri, PA, Zanotta, L, Canziani, A, Roggero, P, Plevani, L, Bertoli, D, Zorzan, S, Giannì, ML, Mosca, F. Do a Few Weeks Matter? Late Preterm Infants and Breastfeeding Issues. Nutrients. 2019. 11:312. doi:10.3390/nu11020312. | Country
248 | Cross-Barnet, C, Augustyn, M, Gross, S, Resnik, A, Paige, D. Long-term breastfeeding support: failing mothers in need. Matern Child Health J. 2012. 16:1926-32. doi:10.1007/s10995-011-0939-x. | Study participants
249 | Crossley, ML. Breastfeeding as a Moral Imperative: An Autoethnographic Study. Feminism & Psychology. 2009. 19:71-87. doi:10.1177/0959353508098620. | Country
250 | Crume, TL, Juhl, AL, Brooks-Russell, A, Hall, KE, Wymore, E, Borgelt, LM. Cannabis Use During the Perinatal Period in a State With Legalized Recreational and Medical Marijuana: The Association Between Maternal Characteristics, Breastfeeding Patterns, and Neonatal Outcomes. J Pediatr. 2018. 197:90-96. doi:10.1016/j.jpeds.2018.02.005. | Mediators/moderators; Intervention/exposure - KQ3
251 | Cueva, K, Shimer, S, Kent, D, Geller, AC, Viswanath, K, Fung, TT. Strengths and Challenges of the Alaska WIC Breastfeeding Peer Counselor Program: A Qualitative Study of Program Implementation. J Nutr Educ Behav. 2017. 49:858-866.e1. doi:10.1016/j.jneb.2017.07.007. | Independent variable - KQ2; Study participants
252 | Cunningham, EM, Doyle, EI, Bowden, RG. Maternity Nurses’ Perceptions of Implementation of the Ten Steps to Successful Breastfeeding. MCN Am J Matern Child Nurs. 2018. 43:38-43. doi:10.1097/nmc.0000000000000392. | Study participants
253 | da Conceição Griffin, CM, Costa Amorim, MH, de Amorim Almeida, F, Oliveira Marcacine, K, Erlach Goldman, R, Pereira Coca, K. LATCH as a systematic tool for assessment of the breastfeeding technique in maternity. Acta Paulista de Enfermagem. 2022. 35:1-9. doi:10.37689/acta-ape/2022AO03181. | Country
254 | da Silva, LR, da Cruz, LA, Macedo, EC, da Silva, LR, Gomes, MN. The Influence Of Grandmothers On Breastfeeding Of Her Grandchildren: Beliefs And Cultural Practices. Revista de Pesquisa: Cuidado e Fundamental. 2013. 5:643-651. doi:10.9789/2175-5361.2013v5n4p643. | Country
255 | Dabritz, HA, Hinton, BG, Babb, J. Evaluation of lactation support in the workplace or school environment on 6-month breastfeeding outcomes in Yolo County, California. J Hum Lact. 2009. 25:182-93. doi:10.1177/0890334408328222. | Study participants
256 | Dagher, RK, McGovern, PM, Dowd, BE, Lundberg, U. Postpartum depressive symptoms and the combined load of paid and unpaid work: a longitudinal analysis. Int Arch Occup Environ Health. 2011. 84:735-43. doi:10.1007/s00420-011-0626-7. | Outcome
257 | Dagher, RK, McGovern, PM, Schold, JD, Randall, XJ. Determinants of breastfeeding initiation and cessation among employed mothers: a prospective cohort study. BMC Pregnancy Childbirth. 2016. 16:194. doi:10.1186/s12884-016-0965-1. | Mediators/moderators; Intervention/exposure - KQ3; Study participants
258 | DaMota, K, Bañuelos, J, Goldbronn, J, Vera-Beccera, LE, Heinig, MJ. Maternal request for in-hospital supplementation of healthy breastfed infants among low-income women. J Hum Lact. 2012. 28:476-82. doi:10.1177/0890334412445299. | Intervention/exposure - KQ3; Independent variable - KQ2
259 | Danielson, RA, Wallenborn, JT, Warne, DK, Masho, SW. Disparities in Risk Factors and Birth Outcomes Among American Indians in North Dakota. Matern Child Health J. 2018. 22:1519-1525. doi:10.1007/s10995-018-2551-9. | Mediators/moderators; Intervention/exposure - KQ3
260 | Darfour-Oduro, SA, Kim, J. WIC mothers’ social environment and postpartum health on breastfeeding initiation and duration. Breastfeed Med. 2014. 9:524-9. doi:10.1089/bfm.2014.0067. | Mediators/moderators; Intervention/exposure - KQ3
261 | D’Artibale, EF, Bercini, LO. Early contact and breastfeeding in a baby friendly hospital. Online Brazilian Journal of Nursing. 2013. 12:587-589. doi:10.5935/1676-4285.20134095. | Country
262 | Dauphin, C, Clark, N, Cadzow, R, Saad-Harfouche, F, Rodriguez, E, Glaser, K, Kiviniemi, M, Keller, M, Erwin, D. #BlackBreastsMatter: Process Evaluation of Recruitment and Engagement of Pregnant African American Women for a Social Media Intervention Study to Increase Breastfeeding. J Med Internet Res. 2020. 22:e16239. doi:10.2196/16239. | Outcome
263 | Davie, P, Bick, D, Pasupathy, D, Norton, S, Chilcot, J. Infant feeding practices among macrosomic infants: A prospective cohort study. Maternal and Child Nutrition. 2021. 17:11. doi:10.1111/mcn.13222. | Country
264 | de Fátima Fernandes Santos Silva, M, Barbosa Pereira, L, Nunes Ferreira, T, Maciel de Souza, AA. Breastfeeding self-efficacy and interrelated factors. Rev Rene. 2018. 19:1-7. doi:10.15253/2175-6783.2018193175. | Country
265 | de Mendoza, VB, Harville, E, Theall, K, Buekens, P, Chasan-Taber, L. Acculturation and Intention to Breastfeed among a Population of Predominantly Puerto Rican Women. Birth-Issues in Perinatal Care. 2016. 43:78-85. doi:10.1111/birt.12199. | Outcome
266 | de Montigny, F, Lacharité, C, Devault, A. Transition to fatherhood: modeling the experience of fathers of breastfed infants. Advances in Nursing Science. 2012. 35:E11-22. doi:10.1097/ans.0b013e3182626167. | Country
267 | de Morais Alves, TR, Nunes de Miranda, FA, Santos Silva, GW, Bittencourt Leite de Carvalho, J, Nogueira Valenca, C, Diniz Cavalcante, R. The female imagery and its invisibility in exclusive breastfeeding: an exploratory study. Online Brazilian Journal of Nursing. 2016. 15:325-335. | Country
268 | de Oliveira, DM, Dahan, P, Ferreira, DF, de Oliveira, LF, de Paula, LI, de Figueiredo, AA, de Bessa, J, Jr, Bastos Netto, JM. Association between exclusive maternal breastfeeding during the first 4 months of life and primary enuresis. J Pediatr Urol. 2016. 12:95.e1-6. doi:10.1016/j.jpurol.2015.07.008. | Country
269 | de Sousa Nobre, R, de Sousa Franco, M, Barros de Sousa, G, da Silva Leão, MK, Santos do Vale, H, de Oliveira Lima, LH. Knowledge Of Students About Breastfeeding. Journal of Nursing UFPE / Revista de Enfermagem UFPE. 2019. 13:1061-1067. doi:10.5205/1981-8963.2019.241927. | Country
270 | Delle Donne, A, Hatch, A, Carr, NR, Aden, J, Shapiro, J. Extended Maternity Leave and Breastfeeding in Active Duty Mothers. Pediatrics. 2019. 144:e20183795. doi:10.1542/peds.2018-3795. | Mediators/moderators; Study participants
271 | Deming, DM, Briefel, RR, Reidy, KC. Infant feeding practices and food consumption patterns of children participating in WIC. J Nutr Educ Behav. 2014. 46:S29-37. doi:10.1016/j.jneb.2014.02.020. | Mediators/moderators; Study participants
272 | Demirci, J, Caplan, E, Murray, N, Cohen, S. “I Just Want to Do Everything Right:” Primiparous Women’s Accounts of Early Breastfeeding via an App-Based Diary. J Pediatr Health Care. 2018. 32:163-172. doi:10.1016/j.pedhc.2017.09.010. | Study participants
273 | Demirci, JR, Bogen, DL. Feasibility and acceptability of a mobile app in an ecological momentary assessment of early breastfeeding. Matern Child Nutr. 2017. 13:e12342. doi:10.1111/mcn.12342. | Study participants
274 | Demirci, JR, Glasser, M, Fichner, J, Caplan, E, Himes, KP. “It gave me so much confidence”: First-time U.S. mothers’ experiences with antenatal milk expression. Matern Child Nutr. 2019. 15:e12824. doi:10.1111/mcn.12824. | Study participants
275 | Demirci, JR, Suffoletto, B, Doman, J, Glasser, M, Chang, JC, Sereika, SM, Bogen, DL. The Development and Evaluation of a Text Message Program to Prevent Perceived Insufficient Milk Among First-Time Mothers: Retrospective Analysis of a Randomized Controlled Trial. JMIR Mhealth Uhealth. 2020. 8:e17328. doi:10.2196/17328. | Outcome
276 | Dennison, BA, Nguyen, TQ, Gregg, DJ, Fan, W, Xu, C. The Impact of Hospital Resources and Availability of Professional Lactation Support on Maternity Care: Results of Breastfeeding Surveys 2009-2014. Breastfeed Med. 2016. 11:479-486. doi:10.1089/bfm.2016.0072. | Outcome
277 | Dennison, BA, Nguyen, TQ, Xu, C, Fan, W, Jurkowski, JM. Impact of State Legislation on Hospital Breastfeeding Support in New York. J Public Health Manag Pract. 2017. 23:e1-e9. doi:10.1097/phh.0000000000000438. | Outcome
278 | Dereddy, NR, Talati, AJ, Smith, A, Kudumula, R, Dhanireddy, R. A multipronged approach is associated with improved breast milk feeding rates in very low birth weight infants of an inner-city hospital. J Hum Lact. 2015. 31:43-6. doi:10.1177/0890334414554619. | Mediators/moderators; Study participants
279 | Dettwyler, Katherine. Full-term Breastfeeding. AIMS Journal. 2013. 25:6-7. | Study design
280 | DeVane-Johnson, S, Wright, YJ, Godwin, L, Williams, JM. Breast-Feeding and Practice Tips for Case Managers. Professional Case Management. 2018. 23:158-162. doi:10.1097/NCM.0000000000000291. | Study design
281 | Devendorf, L, Andersen, K, Kelliher, A. The Fundamental Uncertainties of Mothering: Finding Ways to Honor Endurance, Struggle, and Contradiction. Acm Transactions on Computer-Human Interaction. 2020. 27:24. doi:10.1145/3397177. | Outcome
282 | Dias de Oliveira, L, Justo Giugliani, ER, Córdova do Espírito Santo, L, Meirelles Nunes, L. Counselling sessions increased duration of exclusive breastfeeding: a randomized clinical trial with adolescent mothers and grandmothers. Nutr J. 2014. 13:73. doi:10.1186/1475-2891-13-73. | Country
283 | Díaz Meneses, G. Breastfeeding: an emotional instinct. Breastfeeding Medicine. 2013. 8:191-197. doi:10.1089/bfm.2012.0079. | Country
284 | DiCioccio, HC, Ady, C, Bena, JF, Albert, NM. Initiative to Improve Exclusive Breastfeeding by Delaying the Newborn Bath. J Obstet Gynecol Neonatal Nurs. 2019. 48:189-196. doi:10.1016/j.jogn.2018.12.008. | Independent variable - KQ2; Study participants
285 | Dinour, L, Bai, Y. Is Breast Best? Knowledge and Attitudes of Breastfeeding and Lactation Supports on a University Campus…Food & Nutrition Conference & Expo, 26-29 October 2019, Philadelphia, PA. Journal of the Academy of Nutrition & Dietetics. 2019. 119:A67-A67. doi:10.1016/j.jand.2019.06.190. | Publication status
286 | Dinour, LM, Bai, YK. Breastfeeding: The Illusion of Choice. Womens Health Issues. 2016. 26:479-82. doi:10.1016/j.whi.2016.06.002. | Study design
287 | Dinour, LM, Pope, GA, Bai, YK. Breast milk pumping beliefs, supports, and barriers on a university campus. J Hum Lact. 2015. 31:156-65. doi:10.1177/0890334414557522. | Intervention/exposure - KQ3; Independent variable - KQ2
288 | Dinour, LM, Rivera Rodas, EI, Amutah-Onukagha, NN, Doamekpor, LA. The role of prenatal food insecurity on breastfeeding behaviors: findings from the United States pregnancy risk assessment monitoring system. Int Breastfeed J. 2020. 15:30. doi:10.1186/s13006-020-00276-x. | Mediators/moderators; Intervention/exposure - KQ3
289 | Dinour, LM. Infant Feeding Tracker Applications: Cross-Sectional Analysis of Use. J Nutr Educ Behav. 2022. 54:835-43. doi:10.1016/j.jneb.2022.03.012. | Independent variable - KQ2; Study participants
290 | Dixit, A, Feldman-Winter, L, Szucs, KA. “Frustrated,” “depressed,” and “devastated” pediatric trainees: US academic medical centers fail to provide adequate workplace breastfeeding support. J Hum Lact. 2015. 31:240-8. doi:10.1177/0890334414568119. | Mediators/moderators; Intervention/exposure - KQ3
291 | Dixit, A, Feldman-Winter, L, Szucs, KA. Parental Leave Policies and Pediatric Trainees in the United States. J Hum Lact. 2015. 31:434-9. doi:10.1177/0890334415585309. | Outcome
292 | Doan, T, Gay, CL, Kennedy, HP, Newman, J, Lee, KA. Nighttime breastfeeding behavior is associated with more nocturnal sleep among first-time mothers at one month postpartum. J Clin Sleep Med. 2014. 10:313-9. doi:10.5664/jcsm.3538. | Outcome
293 | Doan, THD. Breastfeeding behavior and related factors in low-income and ethnically diverse mother-infant dyads. University of California, San Francisco; 2009. | Publication status
294 | Dodgson, JE. Considering Inequities in Breastfeeding. J Hum Lact. 2017. 33:248-249. doi:10.1177/0890334417699164. | Study design
295 | Dodt, RC, Joventino, ES, Aquino, PS, Almeida, PC, Ximenes, LB. An experimental study of an educational intervention to promote maternal self-efficacy in breastfeeding. Rev Lat Am Enfermagem. 2015. 23:725-32. doi:10.1590/0104-1169.0295.2609. | Country
296 | dos Santos Bernardo, FM, Chaves Rouberte, ES, Chaves Costa, E, Carvalho De Sousa, VE, Rodrigues Ferreira, AC, de Araújo, TM, Freitas Leal, FK, da Silva Ferreira, D. Care For Lactating Mothers In Puericulture Consultations: Intervention In The Waiting Room. Journal of Nursing UFPE / Revista de Enfermagem UFPE. 2017. 11:5129-5138. doi:10.5205/1981-8963-v11i12a25152p5129-5138-2017. | Country
297 | Douglas, J. The healthiest state in the nation: vermont embraces breastfeeding. Breastfeeding Medicine. 2010. 5:189-190. doi:10.1089/bfm.2010.0073. | Study design
298 | Dowling, DA, Shapiro, J, Burant, CJ, Elfettoh, AA. Factors influencing feeding decisions of black and white mothers of preterm infants. J Obstet Gynecol Neonatal Nurs. 2009. 38:300-9. doi:10.1111/j.1552-6909.2009.01018.x. | Study Participants
299 | Dozier, AM, Brownell, EA, Thevenet-Morrison, K, Martin, H, Hagadorn, JI, Howard, C. Predicting Maintenance of Any Breastfeeding from Exclusive Breastfeeding Duration: A Replication Study. J Pediatr. 2018. 203:197-203.e2. doi:10.1016/j.jpeds.2018.07.100. | Intervention/exposure - KQ3; Independent variable - KQ2
300 | Dozier, AM, Dozier, AM. Community engagement and dissemination of effective breastfeeding programs. Breastfeeding Medicine. 2010. 5:215-216. doi:10.1089/bfm.2010.0051. | Outcome
301 | Dozier, AM, Howard, CR, Brownell, EA, Wissler, RN, Glantz, JC, Ternullo, SR, Thevenet-Morrison, KN, Childs, CK, Lawrence, RA. Labor epidural anesthesia, obstetric factors and breastfeeding cessation. Matern Child Health J. 2013. 17:689-98. doi:10.1007/s10995-012-1045-4. | Mediators/moderators; Intervention/exposure - KQ3
302 | Dozier, AM, McKee, KS. State breastfeeding worksite statutes.…breastfeeding rates…and.…. Breastfeed Med. 2011. 6:319-24. doi:10.1089/bfm.2011.0082. | Mediators/moderators; Study participants
303 | Dozier, AM, Nelson, Alice, Brownell, EA, Howard, CR, Lawrence, RA. Patterns of Postpartum Depot Medroxyprogesterone Administration Among Low-Income Mothers. Journal of Women’s Health (15409996). 2014. 23:224-230. doi:10.1089/jwh.2012.4016. | Outcome
304 | Drago, R. The WIC Program: an economic analysis of breastfeeding and infant formula. Breastfeed Med. 2011. 6:281-6. doi:10.1089/bfm.2011.0070. | Study design
305 | Ducharme-Smith, K, Gross, SM, Resnik, A, Rosenblum, N, Dillaway, C, Orta Aleman, D, Augustyn, M, Silbert-Flagg, J, Caulfield, LE. Exposure to Baby-Friendly Hospital Practices and Breastfeeding Outcomes of WIC Participants in Maryland. J Hum Lact. 2022. 38:78-88. doi:10.1177/0890334421993771. | Independent variable - KQ2; Study participants
306 | Duffy, KD. The maternal themes of meaning for increased breastfeeding duration: A hermeneutic phenomenological study. University of Phoenix; 2010. | Publication status
307 | Dumont, DM, Wildeman, C, Lee, H, Gjelsvik, A, Valera, P, Clarke, JG. Incarceration, maternal hardship, and perinatal health behaviors. Matern Child Health J. 2014. 18:2179-87. doi:10.1007/s10995-014-1466-3. | Intervention/exposure - KQ3; Independent variable - KQ2
308 | Dumphy, D, Thompson, J, Clark, M. A Breastfeeding Quality Improvement Project in Rural Primary Care. J Hum Lact. 2016. 32:633-641. doi:10.1177/0890334416662240. | Independent variable - KQ2; Study participants
309 | Dunlop, AL, Dretler, AW, Badal, HJ, Logue, KM. Acceptability and potential impact of brief preconception health risk assessment and counseling in the WIC setting. Am J Health Promot. 2013. 27:S58-65. doi:10.4278/ajhp.120109-QUAL-7. | Outcome
310 | Dunn, RL, Kalich, KA, Fedrizzi, R, Phillips, S. Barriers and Contributors to Breastfeeding in WIC Mothers: A Social Ecological Perspective. Breastfeed Med. 2015. 10:493-501. doi:10.1089/bfm.2015.0084. | Mediators/moderators; Intervention/exposure - KQ3
311 | Dunn, RL, Kalich, KA, Henning, MJ, Fedrizzi, R. Engaging field-based professionals in a qualitative assessment of barriers and positive contributors to breastfeeding using the social ecological model. Matern Child Health J. 2015. 19:6-16. doi:10.1007/s10995-014-1488-x. | Study participants
312 | Durmazoğlu, G, Çiçek, Ö, Okumuş, H. The effect of spousal support perceived by mothers on breastfeeding in the postpartum period. Turk Arch Pediatr. 2021. 56:57-61. doi:10.14744/TurkPediatriArs.2020.09076. | Country
313 | Dykes, F, Flacking, R. Encouraging breastfeeding: A relational perspective. Early Hum Dev. 2010. 86:733-6. doi:10.1016/j.earlhumdev.2010.08.004. | Study design
314 | Eagen-Torkko, M, Low, LK, Zielinski, R, Seng, JS. Prevalence and Predictors of Breastfeeding After Childhood Abuse. J Obstet Gynecol Neonatal Nurs. 2017. 46:465-479. doi:10.1016/j.jogn.2017.01.002. | Study participants
315 | Eckhardt, CL, Lutz, T, Karanja, N, Jobe, JB, Maupomé, G, Ritenbaugh, C. Knowledge, attitudes, and beliefs that can influence infant feeding practices in American Indian mothers. J Acad Nutr Diet. 2014. 114:1587-93. doi:10.1016/j.jand.2014.04.021. | Outcome
316 | Eddy, TL. Maternal psychosocial factors related to duration and exclusivity of breastfeeding practices among rural women: The healthy moms and babies study. University of Missouri-Columbia; 2015. | Publication status
317 | Eden, AR, Anstey, EH, Orriola, D. Growing the IBCLC Workforce: A Florida Needs Assessment. J Hum Lact. 2018. 34:148-155. doi:10.1177/0890334417739580. | Outcome
318 | Edwards, RC, Thullen, MJ, Henson, LG, Lee, H, Hans, SL. The association of breastfeeding initiation with sensitivity, cognitive stimulation, and efficacy among young mothers: a propensity score matching approach. Breastfeed Med. 2015. 10:13-9. doi:10.1089/bfm.2014.0123. | Mediators/moderators; Intervention/exposure - KQ3
319 | Eganhouse, DJ, Gutierrez, L, Cuellar, L, Velasquez, C. Becoming Baby-Friendly and Transforming Maternity Care in a Safety-Net Hospital on the Texas-Mexico Border. Nurs Womens Health. 2016. 20:378-90. doi:10.1016/j.nwh.2016.07.005. | Outcome
320 | Eidelman, AI. Impact of Refugee Status on Breastfeeding. Breastfeeding Medicine. 2020. 15:425-425. doi:10.1089/bfm.2020.29156.aie. | Study design
321 | Eidelman, AI. Racial disparities in breastfeeding--a continuing shame of our healthcare system. Breastfeed Med. 2015. 10:185-185. doi:10.1089/bfm.2015.9990. | Study design
322 | Eidelman, AI. The tragedy/comedy of not breastfeeding. Breastfeeding Medicine. 2013. 8:143-144. doi:10.1089/bfm.2013.9996. | Study design
323 | Eilers, MA, Hendrick, CE, Pérez-Escamilla, R, Powers, DA, Potter, JE. Breastfeeding Initiation, Duration, and Supplementation Among Mexican-Origin Women in Texas. Pediatrics. 2020. 145: e20192742. doi:10.1542/peds.2019-2742. | Intervention/exposure - KQ3; Study participants
324 | Ekström-Bergström, A, Thorstensson, S, Bäckström, C. The concept, importance and values of support during childbearing and breastfeeding – A discourse paper. Nursing Open. 2022. 9:156-167. doi:10.1002/nop2.1108. | Country; Study design
325 | El-Bayoumi, J. Why Should We Care About Health Equity?. Breastfeed Med. 2017. 12:462-464. doi:10.1089/bfm.2017.0131. | Study design
326 | Eldridge, JD, Hartnett, JO, Lee, FF, Sekhobo, JP, Edmunds, LS. Implementing a WIC-Based Intervention to Promote Exclusive Breastfeeding: Challenges, Facilitators, and Adaptive Strategies. J Nutr Educ Behav. 2017. 49:S177-S185.e1. doi:10.1016/j.jneb.2017.04.005. | Outcome; Data type
327 | Elfgen, C, Hagenbuch, N, Görres, G, Block, E, Leeners, B. Breastfeeding in Women Having Experienced Childhood Sexual Abuse. Journal of Human Lactation. 2017. 33:119-127. doi:10.1177/0890334416680789. | Country
328 | Entwistle, F, Kendall, S, Mead, M. Breastfeeding support - the importance of self-efficacy for low-income women. Matern Child Nutr. 2010. 6:228-42. doi:10.1111/j.1740-8709.2009.00202.x. | Country
329 | Ersen, G, Kasim, I, Agadayi, E, Demir Alsancak, A, Sengezer, T, Ozkara, A. Factors Affecting the Behavior and Duration of Breastfeeding Among Physician Mothers. J Hum Lact. 2020. 36:471-477. doi:10.1177/0890334419892257. | Country
330 | Esquerra-Zwiers, A, Goris, ED, Franzen, A. Explaining variance in breastfeeding intentions and behaviors among a cohort of Midwest mothers using a theory of planned behavior-based structural model. BMC Pregnancy Childbirth. 2022. 22:314. doi:10.1186/s12884-022-04628-9. | Mediators/moderators; Intervention/exposure - KQ3; Study participants
331 | Esquerra-Zwiers, A, Schoeny, ME, Engstrom, J, Wicks, J, Szotek, J, Meier, P, Patel, AL. The Interaction of Donor Human Milk Availability and Race/Ethnicity on Provision of Mother’s Own Milk for Very Low Birth Weight Infants. Breastfeed Med. 2021. 16:46-53. doi:10.1089/bfm.2020.0212. | Study participants
332 | Etowa, J, Etowa, E, Nare, H, Mbagwu, I, Hannan, J. Social Determinants of Breastfeeding Preferences among Black Mothers Living with HIV in Two North American Cities. Int J Environ Res Public Health. 2020. 17: 6893. doi:10.3390/ijerph17186893. | Mediators/moderators; Intervention/exposure - KQ3
333 | Ettienne-Gittens, R, McKyer, EL, Odum, M, Diep, CS, Li, Y, Girimaji, A, Murano, PS. Rural versus urban Texas WIC participants’ fruit and vegetable consumption. Am J Health Behav. 2013. 37:130-40. doi:10.5993/ajhb.37.1.15. | Outcome
334 | Evans, K, Labbok, M, Abrahams, SW. WIC and breastfeeding support services: does the mix of services offered vary with race and ethnicity?. Breastfeed Med. 2011. 6:401-6. doi:10.1089/bfm.2010.0086. | Outcome; Study participants
335 | Fabiyi, C, Rankin, K, Norr, K, Yoder, JC, Vasa, R, White-Traut, R. The Association of Low Social Support with Breast Milk Expression in Low-Income Mother-Preterm Infant Dyads. J Hum Lact. 2015. 31:490-7. doi:10.1177/0890334415586199. | Mediators/moderators; Intervention/exposure - KQ3
336 | Fadel, CW, Colson, ER, Corwin, MJ, Rybin, D, Heeren, TC, Wang, C, Moon, RY. Maternal Attitudes and Other Factors Associated with Infant Vaccination Status in the United States, 2011-2014. J Pediatr. 2017. 185:136-142.e1. doi:10.1016/j.jpeds.2017.02.012. | Outcome
337 | Faircloth, CR. ‘If they want to risk the health and well-being of their child, that’s up to them’: Long-term breastfeeding, risk and maternal identity. Health Risk & Society. 2010. 12:357-367. doi:10.1080/13698571003789674. | Country
338 | Fairlie, TG, Gillman, MW, Rich-Edwards, J. High Pregnancy-Related Anxiety and Prenatal Depressive Symptoms as Predictors of Intention to Breastfeed and Breastfeeding Initiation. Journal of Womens Health. 2009. 18:945-953. doi:10.1089/jwh.2008.0998. | Mediators/moderators; Intervention/exposure - KQ3
339 | Fam, J, Chen, H, Wang, JM. Supportive counseling for postpartum depression in Asian mothers. Asia-Pacific Psychiatry. 2011. 3:61-66. doi:10.1111/j.1758-5872.2011.00122.x. | Country
340 | Farokhi, MR, Cano, SM, Bober-Moken, IG, Bartoloni, JA, Cunningham, SE, Baez, MX. Maternal acculturation: could it impact oral health practices of mexican-american mothers and their children?. J Prim Care Community Health. 2011. 2:87-95. doi:10.1177/2150131910388942. | Mediators/moderators; Intervention/exposure - KQ3
341 | Farr, RS, Rahman, F, O’Riordan, MA, Furman, L. Assessing the Feasibility and Effectiveness of Two Prenatal Breastfeeding Intervention Apps in Promoting Postpartum In-Hospital Exclusive Breastfeeding. Breastfeed Med. 2019. 14:724-730. doi:10.1089/bfm.2019.0053. | Mediators/moderators; Comparator - KQ3
342 | Fastring, D, Mayfield-Johnson, S, Madison, J. Evaluation of a Health Education Intervention to Improve Knowledge, Skills, Behavioral Intentions and Resources Associated with Preventable Determinants of Infant Mortality. Divers Equal Health Care. 2017. 14:290-295. | Outcome
343 | Feenstra, MM, Jørgine Kirkeby, M, Thygesen, M, Danbjørg, DB, Kronborg, H. Early breastfeeding problems: A mixed method study of mothers’ experiences. Sex Reprod Healthc. 2018. 16:167-174. doi:10.1016/j.srhc.2018.04.003. | Country
344 | Felder, T, Jackson, J, McGrievy, M, Tucker, C, Jasper, C. Evaluation of a Mobile Web Site Application to Promote Breastfeeding Among African American Women…2020 Association of Women’s Health, Obstetric and Neonatal Nurses (AWHONN) Annual Convention, Nov 1-4, 2020. JOGNN: Journal of Obstetric, Gynecologic & Neonatal Nursing. 2020. 49:S6-S7. doi:10.1016/j.jogn.2020.09.013. | Publication status
345 | Felice, JP, Geraghty, SR, Quaglieri, CW, Yamada, R, Wong, AJ, Rasmussen, KM. “Breastfeeding” without baby: A longitudinal, qualitative investigation of how mothers perceive, feel about, and practice human milk expression. Matern Child Nutr. 2017. 13:e12426. doi:10.1111/mcn.12426. | Intervention/exposure - KQ3; Independent variable - KQ2
346 | Felice, JP, Cassano, PA, Rasmussen, KM. Pumping human milk in the early postpartum period: its impact on long-term practices for feeding at the breast and exclusively feeding human milk in a longitudinal survey cohort. American Journal of Clinical Nutrition. 2016. 103:1267-1277. doi:10.3945/ajcn.115.115733. | Intervention/exposure - KQ3; Independent variable - KQ2
347 | Fernandes do Carmo Souza, E, Quintella Fernandes, RÁ. Breastfeeding self-efficacy: a cohort study. Acta Paulista de Enfermagem. 2014. 27:465-470. doi:10.1590/1982-0194201400076. | Country
348 | Fernandes, RC, Höfelmann, DA. Intention to breastfeed among pregnant women: association with work, smoking, and previous breastfeeding experience. Cien Saude Colet. 2020. 25:1061-1072. doi:10.1590/1413-81232020253.27922017. | Country
349 | Fernandes, VMB, Santos, Ekad, Erdmann, AL, Pires, DEP, Zampieri, MFM, Gregório, VRP. Establishment of lactaton rooms in public and private companies: potentialities and difficulties. Rev Gaucha Enferm. 2017. 37:e201600446. doi:10.1590/1983-1447.2016.esp.2016-0046. | Country
350 | Fernández Medina, IM, Fernández-Sola, C, López-Rodríguez, MM, Hernández-Padilla, JM, Jiménez Lasserrotte, MDM, Granero-Molina, J. Barriers to Providing Mother’s Own Milk to Extremely Preterm Infants in the NICU. Adv Neonatal Care. 2019. 19:349-360. doi:10.1097/anc.0000000000000652. | Country
351 | Fernández-Cañadas Morillo, A, Durán Duque, M, Hernández López, AB, Muriel Miguel, C, Martínez Rodríguez, B, Oscoz Prim, A, Pérez Riveiro, P, Salcedo Mariña, A, Royuela Vicente, A, Casillas Santana, ML, Marín Gabriel, MA. A Comparison of Factors Associated with Cessation of Exclusive Breastfeeding at 3 and 6 Months. Breastfeed Med. 2017. 12:430-435. doi:10.1089/bfm.2017.0045. | Country
352 | Fernández-Cañadas Morillo, A, Durán Duque, M, Hernández López, AB, Muriel Miguel, C, Pérez Riveiro, P, Salcedo Mariña, A, Royuela Vicente, A, Casillas Santana, ML, Marín Gabriel, MA. Cessation of breastfeeding in association with oxytocin administration and type of birth. A prospective cohort study. Women & Birth. 2019. 32:e43-e48. doi:10.1016/j.wombi.2018.04.017. | Country
353 | Ferreira, EC, Costa, ML, Pacagnella, RC, Silveira, C, Andreucci, CB, Zanardi, DM, Santos, JP, Angelini, CR, Souza, RT, Parpinelli, MA, Sousa, MH, Cecatti, JG. General and reproductive health among women after an episode of severe maternal morbidity: Results from the COMMAG study. Int J Gynaecol Obstet. 2020. 150:83-91. doi:10.1002/ijgo.13161. | Country
354 | Fessenden, M. His milk, her milk. Milk composition differs based on a baby’s sex and a mother’s wealth. Scientific American. 2012. 307:20-20. | Country; Publication status
355 | Figueiredo, B, Canário, C, Field, T. Breastfeeding is negatively affected by prenatal depression and reduces postpartum depression. Psychological Medicine. 2014. 44:927-936. doi:10.1017/S0033291713001530. | Country
356 | Figueredo, SF, Mattar, MJG, de Vilhena Abrão, ACF. Baby-Friendly Hospital: prevalence of exclusive breastfeeding at 6 months and intervening factors. Revista da Escola de Enfermagem da USP. 2013. 47:1291-1297. doi:10.1590/S0080-623420130000600006. | Country
357 | Finigan, V. Breastfeeding and diabetes: part 1. Pract Midwife. 2012. 15:28, 30-2. | Study design
358 | Finigan, V. Breastfeeding and diabetes: Part 2. Pract Midwife. 2012. 15:33-4, 36. | Study design
359 | Fitzpatrick, E, Dennison, BA, Welge, SB, Hisgen, S, Boyce, PS, Waniewski, PA. Development of the breastfeeding quality improvement in hospitals learning collaborative in new york state. Breastfeeding Medicine. 2013. 8:263-272. doi:10.1089/bfm.2012.0107. | Independent variable - KQ2; Study participants
360 | Flaherman, VJ, Fuentes-Afflick, E. Social and public health perspectives of promotion of breastfeeding. JAMA Pediatrics. 2014. 168:877-878. doi:10.1001/jamapediatrics.2014.907. | Study design
361 | Flaherman, VJ, McKean, M, Braunreuther, E, Kair, LR, Cabana, MD. Minimizing the Relationship Between Early Formula Use and Breastfeeding Cessation by Limiting Formula Volume. Breastfeeding Medicine. 2019. 14:533-537. doi:10.1089/bfm.2019.0055. | Mediators/moderators; Study participants
362 | Flaherman, VJ, Cabana, MD, McCulloch, CE, Paul, IM. Effect of Early Limited Formula on Breastfeeding Duration in the First Year of Life: A Randomized Clinical Trial. JAMA Pediatr. 2019. 173:729-735. doi:10.1001/jamapediatrics.2019.1424. | Mediators/moderators; Study participants
363 | Flaherman, VJ, Gay, B, Scott, C, Avins, A, Lee, KA, Newman, TB. Randomised trial comparing hand expression with breast pumping for mothers of term newborns feeding poorly. Archives of Disease in Childhood-Fetal and Neonatal Edition. 2012. 97:F18-F23. doi:10.1136/adc.2010.209213. | Independent variable - KQ2; Study participants
364 | Fleurant, E, Schoeny, M, Hoban, R, Asiodu, IV, Riley, B, Meier, PP, Bigger, H, Patel, AL. Barriers to Human Milk Feeding at Discharge of Very-Low-Birth-Weight Infants: Maternal Goal Setting as a Key Social Factor. Breastfeed Med. 2017. 12:20-27. doi:10.1089/bfm.2016.0105. | Study Participants
365 | Flood, JL, Dodgson, JE. Health care and social service providers’ descriptions of pacific islander mothers’ breastfeeding patterns. J Midwifery Womens Health. 2010. 55:162-70. doi:10.1016/j.jmwh.2009.04.009. | Outcome; Study participants
366 | Flood, JL. Breastfeeding patterns in the rural community of Hilo, Hawai’i: an exploration of existing data sets. Hawaii J Med Public Health. 2013. 72:81-6. | Mediators/moderators; Intervention/exposure - KQ3; Study participants
367 | Flores, A, Anchondo, I, Huang, C, Villanos, M, Finch, C. “Las Dos Cosas,” or Why Mexican American Mothers Breast-Feed, But Not for Long. South Med J. 2016. 109:42-50. doi:10.14423/smj.0000000000000400. | Study participants
368 | Flores, G. Devising, implementing, and evaluating interventions to eliminate health care disparities in minority children. Pediatrics. 2009. 124 Suppl 3:S214-23. doi:10.1542/peds.2009-1100J. | Study design
369 | Fornasaro-Donahue, VM, Tovar, A, Sebelia, L, Greene, GW. Increasing breastfeeding in WIC participants: cost of formula as a motivator. J Nutr Educ Behav. 2014. 46:560-9. doi:10.1016/j.jneb.2014.03.003. | Mediators/moderators; Intervention/exposure - KQ3
370 | Foster, HW. Increasing breastfeeding: challenges and opportunities. Breastfeed Med. 2009. 4 Suppl 1:S63-5. doi:10.1089/bfm.2009.0038. | Study design
371 | Francis, J, Unger, S, Bando, N, Vance, A, Gibbins, S, Kiss, A, Church, P, Sellen, D, O’Connor, DL. Postdischarge Feeding of Very-low-birth-weight Infants: Adherence to Nutrition Guidelines. J Pediatr Gastroenterol Nutr. 2018. 67:401-408. doi:10.1097/mpg.0000000000002041. | Country
372 | Fraser, Melanie. Law and breastfeeding. MIDIRS Midwifery Digest. 2010. 20:493-497. | Country; Study design
373 | Frazier, CM, Dharod, J, Labban, J, Raynor, AN, Villasenor, M, Hernandez, M, Ramos-Castillo, I. Breastfeeding: How is it related to food insecurity and other factors among low-income mothers?. Health Care Women Int. 2021. 1-12. doi:10.1080/07399332.2021.1929992. | Mediators/moderators; Intervention/exposure - KQ3
374 | Friesen, CA, Hormuth, LJ, Curtis, TJ. The Bosom Buddy Project: A Breastfeeding Support Group Sponsored by the Indiana Black Breastfeeding Coalition for Black and Minority Women in Indiana. J Hum Lact. 2015. 31:587-91. doi:10.1177/0890334415581617. | Outcome
375 | Friesen, CA, Hormuth, LJ, Petersen, D, Babbitt, T. Using Videoconferencing Technology to Provide Breastfeeding Support to Low-Income Women: Connecting Hospital-Based Lactation Consultants with Clients Receiving Care at a Community Health Center. J Hum Lact. 2015. 31:595-9. doi:10.1177/0890334415601088. | Outcome; Comparator
376 | Friesen, CA, Hormuth, LJ, Cardarelli, TL. Community-Based Participatory Initiatives to Increase Breastfeeding Rates in Indiana. Journal of Human Lactation. 2015. 31:600-606. doi:10.1177/0890334415599974. | Outcome
377 | Frigo, J, Antunes Zocche, D, Silveira, S, Marin, SM, de Jesus Hernández Rodriguez, M, Ledra, FF. Perceptions of the bearers of HIV/AIDS before the inability to breastfeeding. Revista de Pesquisa: Cuidado e Fundamental. 2014. 6:627-636. doi:10.9789/2175-5361.2014v6n2p627. | Country
378 | Froh, EB, Cascino, A, Cerreta, SK, Karsch, EA, Kornberg, LF, Lilley, JE, Welch, L, Spatz, DL. Status of Legislative Efforts to Promote and Protect Breastfeeding and the Provision of Human Milk for Women Returning to Work in the First Postpartum Year. Breastfeed Med. 2018. 13:506-509. doi:10.1089/bfm.2018.0092. | Outcome
379 | Froh, EB, Deatrick, JA, Curley, MA, Spatz, DL. Making meaning of pumping for mothers of infants with congenital diaphragmatic hernia. J Obstet Gynecol Neonatal Nurs. 2015. 44:439-49. doi:10.1111/1552-6909.12564. | Study participants
380 | Froh, EB, Spatz, DL. Navigating Return to Work and Breastfeeding in a Hospital with a Comprehensive Employee Lactation Program. J Hum Lact. 2016. 32:689-694. doi:10.1177/0890334416663475. | Independent variable - KQ2; Study participants
381 | Fryer, K, Santos, HP, Jr, Pedersen, C, Stuebe, AM. The Hispanic Paradox: Socioeconomic Factors and Race/Ethnicity in Breastfeeding Outcomes. Breastfeed Med. 2018. 13:174-180. doi:10.1089/bfm.2017.0157. | Mediators/moderators; Intervention/exposure - KQ3
382 | Fuell Wysong, E, Tossone, K, Furman, L. Expectant inner-city women: attitudes about contraception given infant feeding choice. Eur J Contracept Reprod Health Care. 2017. 22:369-374. doi:10.1080/13625187.2017.1397110. | Mediators/moderators; Intervention/exposure - KQ3
383 | Fukumoto, E, Fukumoto, S, Kawasaki, K, Furugen, R, Kitamura, M, Kawashita, Y, Hayashida, H, Fukuda, H, Iijima, Y, Saito, T. Cessation Age of Breast-feeding and Pacifier Use is Associated With Persistent Finger-sucking. Pediatric Dentistry. 2013. 35:506-509. | Country
384 | Furman, L, Feinstein, J, Delozier, S. Understanding Breastfeeding Barriers at an Urban Pediatric Practice. J Racial Ethn Health Disparities. 2022. 1-12. doi:10.1007/s40615-022-01248-z. | Intervention/exposure - KQ3; Outcome
385 | Furman, L, Killpack, S, Matthews, L, Davis, V, O’Riordan, MA. Engaging Inner-City Fathers in Breastfeeding Support. Breastfeed Med. 2016. 11:15-20. doi:10.1089/bfm.2015.0092. | Outcome
386 | Furman, L, Matthews, L, Davis, V, Killpack, S, O’Riordan, MA. Breast for Success: A Community-Academic Collaboration to Increase Breastfeeding Among High-Risk Mothers in Cleveland. Prog Community Health Partnersh. 2016. 10:341-353. doi:10.1353/cpr.2016.0041. | Publication status
387 | Furman, LM, Dickinson, C. Community health workers: collaborating to support breastfeeding among high-risk inner-city mothers. Breastfeed Med. 2013. 8:73-8. doi:10.1089/bfm.2012.0027. | Mediators/moderators; Study participants
388 | Gaffney, KF, Brito, AV, Kitsantas, P, Kermer, DA, Pereddo, G, Ramos, KM. Institute of Medicine Early Infant Feeding Recommendations for Childhood Obesity Prevention: Implementation by Immigrant Mothers From Central America. J Pediatr Nurs. 2018. 40:27-33. doi:10.1016/j.pedn.2018.02.017. | Mediators/moderators; Intervention/exposure - KQ3
389 | Gaffney, KF, Kitsantas, P, Brito, A, Swamidoss, CS. Postpartum depression, infant feeding practices, and infant weight gain at six months of age. J Pediatr Health Care. 2014. 28:43-50. doi:10.1016/j.pedhc.2012.10.005. | Mediators/moderators; Intervention/exposure - KQ3
390 | Gaffney, KF, Kitsantas, P, Cheema, J. Clinical practice guidelines for feeding behaviors and weight-for-age at 12 months: a secondary analysis of the Infant Feeding Practices Study II. Worldviews Evid Based Nurs. 2012. 9:234-42. doi:10.1111/j.1741-6787.2011.00236.x. | Outcome
391 | Gallegos, D, Russell-Bennett, R, Previte, J, Parkinson, J. Can a text message a week improve breastfeeding?. BMC Pregnancy Childbirth. 2014. 14:374. doi:10.1186/s12884-014-0374-2. | Country
392 | Gallo, S, Kogan, K, Kitsantas, P. Racial and Ethnic Differences in Reasons for Breastfeeding Cessation Among Women Participating in the Special Supplemental Nutrition Program for Women, Infants, and Children. J Midwifery Womens Health. 2019. 64:725-733. doi:10.1111/jmwh.13031. | Outcome
393 | Gallo, S, Thapa, K, Rajbhandari-Thapa, J. O43 Timing of WIC Enrollment and Exclusive Breastfeeding: Results from the National WIC Infant Toddler Feeding Practices Study 2…Society for Nutrition Education and Behavior Annual Conference (Virtual), 8-10 August, 2021. Journal of Nutrition Education & Behavior. 2021. 53:S20-S21. doi:10.1016/j.jneb.2021.04.052. | Publication status
394 | Ganju, A, Suresh, A, Stephens, J, Palettas, M, Burke, D, Miles, L, Lehman, K, Rudesill, R, Lustberg, M, Bose-Brill, S, Ramaswamy, B. Learning, Life, and Lactation: Knowledge of Breastfeeding’s Impact on Breast Cancer Risk Reduction and Its Influence on Breastfeeding Practices. Breastfeed Med. 2018. 13:651-656. doi:10.1089/bfm.2018.0170. | Mediators/moderators; Intervention/exposure - KQ3
395 | Garner, CD, McKenzie, SA, Devine, CM, Thornburg, LL, Rasmussen, KM. Obese women experience multiple challenges with breastfeeding that are either unique or exacerbated by their obesity: discoveries from a longitudinal, qualitative study. Matern Child Nutr. 2017. 13:e12344. doi:10.1111/mcn.12344. | Study participants
396 | Garrett, CC, Azimov, M, Campwala, K, Sarmiento, M, Linton, KF. Breastfeeding Practices Among Hispanic and Non-Hispanic Women at the Postpartum Visit. J Hum Lact. 2018. 34:485-493. doi:10.1177/0890334418774765. | Mediators/moderators; Intervention/exposure - KQ3
397 | Garvin, CC, Sriraman, NK, Paulson, A, Wallace, E, Martin, CE, Marshall, L. The business case for breastfeeding: a successful regional implementation, evaluation, and follow-up. Breastfeed Med. 2013. 8:413-7. doi:10.1089/bfm.2012.0104. | Outcome
398 | Gate, T. Think Breastfeeding think Arkansas WIC. ASBN Update. 2012. 16:18-20. | Study design
399 | Gee, RE, Zerbib, LD, Luckett, BG. Breastfeeding support for African-American women in Louisiana hospitals. Breastfeed Med. 2012. 7:431-5. doi:10.1089/bfm.2011.0150. | Outcome
400 | Gerchow, L, Squires, A, Jones, S. Disparities in Breastfeeding Duration of New York City Latinx Mothers by Birth Region. Breastfeed Med. 2021. 16:607-613. doi:10.1089/bfm.2021.0030. | Mediators/moderators; Intervention/exposure - KQ3
401 | Gettler, LT, McKenna, JJ. Evolutionary perspectives on mother-infant sleep proximity and breastfeeding in a laboratory setting. Am J Phys Anthropol. 2011. 144:454-62. doi:10.1002/ajpa.21426. | Outcome
402 | Ghazi Sherbaf, F, Lin, DDM, Yousem, DM. Parental Leave Policy in Radiology Residency Programs: Current Status. J Am Coll Radiol. 2020. 17:1163-1171. doi:10.1016/j.jacr.2019.12.032. | Study participants
403 | Giannì, ML, Bezze, E, Sannino, P, Stori, E, Plevani, L, Roggero, P, Agosti, M, Mosca, F. Facilitators and barriers of breastfeeding late preterm infants according to mothers’ experiences. BMC Pediatr. 2016. 16:179. doi:10.1186/s12887-016-0722-7. | Country
404 | Gibby, CLK, Palacios, C, Campos, M, Graulau, RE, Banna, J. Acceptability of a text message-based intervention for obesity prevention in infants from Hawai’i and Puerto Rico WIC. BMC Pregnancy Childbirth. 2019. 19:291. doi:10.1186/s12884-019-2446-9. | Outcome
405 | Gibby, CLK, Palacios, C, Campos, M, Lim, E, Banna, J. Breastfeeding Discontinuation Not Associated with Maternal Pregravid BMI But Associated with Native Hawaiian or Other Pacific Islander Race in Hawaii and Puerto Rico WIC Participants. Matern Child Health J. 2019. 23:19-29. doi:10.1007/s10995-018-2587-x. | Mediators/moderators; Intervention/exposure - KQ3
406 | Gila-Díaz, A, Carrillo, GH, López de Pablo Á, L, Arribas, SM, Ramiro-Cortijo, D. Association between Maternal Postpartum Depression, Stress, Optimism, and Breastfeeding Pattern in the First Six Months. Int J Environ Res Public Health. 2020. 17:7153. doi:10.3390/ijerph17197153. | Country
407 | Gilbert, WM, Bliss, MC, Johnson, A, Farrell, W, Gregg, L, Swanson, C. Improving recording accuracy, transparency, and performance for obstetric quality measures in a community hospital-based obstetrics department. Jt Comm J Qual Patient Saf. 2013. 39:258-66. doi:10.1016/s1553-7250(13)39035-7. | Independent variable - KQ2; Study participants
408 | Giordano, J, Hernandez, N, Gulutz, MA, Neuhaus, B, Anders, M, Thayer, K, Robbins, A, Shulman, VB, Kacinski, C, Gebhart, D, Eckardt, P. Cultivating Better Outcomes for Mothers and Newborns Through Integrated Best Practice Models. JOGNN: Journal of Obstetric, Gynecologic & Neonatal Nursing. 2014. 43:S33-S34. doi:10.1111/1552-6909.12409. | Publication status
409 | Godbout, JM, Goldsberry, WN, Franklin, TE. Factors Associated with Infant Feeding Choices in the Adolescent Population. J Hum Lact. 2016. 32:642-647. doi:10.1177/0890334416662629. | Mediators/moderators; Intervention/exposure - KQ3
410 | Godleski, SA, Shisler, S, Eiden, RD, Schuetze, P. Maternal Smoking and Psychosocial Functioning: Impact on Subsequent Breastfeeding Practices. Breastfeed Med. 2020. 15:246-253. doi:10.1089/bfm.2019.0148. | Intervention/exposure - KQ3; Independent variable - KQ2
411 | Gogel, L, Zielinski, R, Deibel, M, Kothari, C. Improving Maternal and Infant Health through CenteringPregnancy: Results of a 2-Year Retrospective Chart Review Using a Matched Comparison Design. Journal of Midwifery & Women’s Health. 2013. 58:584-585. doi:10.1111/jmwh.12118. | Publication status
412 | Goldbort, J, Bresnahan, M, Zhuang, J, Bogdan-Lovis, E, Park, S. Breastfeeding but not Exclusively: Exploration of Chinese American Mothers’ Infant Feeding Practices. J Hum Lact. 2021. 37:380-389. doi:10.1177/0890334420948451. | Mediators/moderators; Intervention/exposure - KQ3
413 | Gorman, JR, Kao, K, Chambers, CD. Breastfeeding among women exposed to antidepressants during pregnancy. J Hum Lact. 2012. 28:181-8. doi:10.1177/0890334411429782. | Mediators/moderators; Intervention/exposure - KQ3
414 | Gottenborg, E, Maw, A, Ngov, LK, Burden, M, Ponomaryova, A, Jones, CD. You Can’t Have It All: The Experience of Academic Hospitalists During Pregnancy, Parental Leave, and Return to Work. J Hosp Med. 2018. 13:836-839. doi:10.12788/jhm.3076. | Study participants
415 | Gould Rothberg, BE, Magriples, U, Kershaw, TS, Rising, SS, Ickovics, JR. Gestational weight gain and subsequent postpartum weight loss among young, low-income, ethnic minority women. Am J Obstet Gynecol. 2011. 204:52.e1-11. doi:10.1016/j.ajog.2010.08.028. | Outcome
416 | Goulding, AN, Wouk, K, Stuebe, AM. Contraception and Breastfeeding at 4 Months Postpartum Among Women Intending to Breastfeed. Breastfeed Med. 2018. 13:75-80. doi:10.1089/bfm.2017.0064. | Independent variable - KQ2; Study participants
417 | Grant, JH, Handwerk, K, Baker, K, Milling, V, Barlow, S, Vladutiu, CJ. Implementing Group Prenatal Care in Southwest Georgia Through Public-Private Partnerships. Matern Child Health J. 2018. 22:1535-1542. doi:10.1007/s10995-018-2576-0. | Mediators/moderators; Comparator - KQ3
418 | Grassley, JS, Spencer, BS, Bryson, Deborah. The development and psychometric testing of the Supportive Needs of Adolescents Breastfeeding Scale. Journal of Advanced Nursing (John Wiley & Sons, Inc.). 2013. 69:708-716. doi:10.1111/j.1365-2648.2012.06119.x. | Outcome
419 | Gray, KD, Hannon, EA, Erickson, E, Stewart, AB, Wood, CT, Fisher, K, Shaikh, SK, Tanaka, D. Influence of Early Lactation Assistance on Inpatient Exclusive Breastfeeding Rates. J Hum Lact. 2021. 37:556-565. doi:10.1177/0890334420957967. | Mediators/moderators; Study participants
420 | Green, KE. Black mothers’ breastfeeding club: community outreach and active support. Breastfeed Med. 2010. 5:221-2. doi:10.1089/bfm.2010.0031. | Study design
421 | Green, TL, Bodas, MV, Jones, HA, Masho, SW, Hagiwara, N. Disparities in Self-Reported Prenatal Counseling: Does Immigrant Status Matter?. J Community Health. 2018. 43:864-873. doi:10.1007/s10900-018-0495-z. | Mediators/moderators; Intervention/exposure - KQ3
422 | Greenaway, DA. WIC breastfeeding support at risk. Breastfeed Med. 2011. 6:247-8. doi:10.1089/bfm.2011.9983. | Study design
423 | Gregg, DJ, Dennison, BA, Restina, K. Breastfeeding-Friendly Erie County: Establishing a Baby Café Network. J Hum Lact. 2015. 31:592-4. doi:10.1177/0890334415601860. | Outcome
424 | Gregory, EF, Butz, AM, Ghazarian, SR, Gross, SM, Johnson, SB. Met Expectations and Satisfaction with Duration: A Patient-Centered Evaluation of Breastfeeding Outcomes in the Infant Feeding Practices Study II. Journal of Human Lactation. 2015. 31:444-451. doi:10.1177/0890334415579655. | Mediators/moderators; Intervention/exposure - KQ3
425 | Gregory, EF, Gross, SM, Nguyen, TQ, Butz, AM, Johnson, SB. WIC Participation and Breastfeeding at 3 Months Postpartum. Matern Child Health J. 2016. 20:1735-44. doi:10.1007/s10995-016-1977-1. | Mediators/moderators; Study participants
426 | Griauzde, DH, Kieffer, EC, Domoff, SE, Hess, K, Feinstein, S, Frank, A, Pike, D, Pesch, MH. The influence of social media on child feeding practices and beliefs among Hispanic mothers: A mixed methods study. Eat Behav. 2020. 36:101361. doi:10.1016/j.eatbeh.2019.101361. | Intervention/exposure - KQ3; Outcome
427 | Gribble, KD, Gallagher, Morgan. Rights of Children in Relation to Breastfeeding in Child Protection Cases. British Journal of Social Work. 2014. 44:434-450. doi:10.1093/bjsw/bcu004. | Country
428 | Gribble, KD. Writing Expert Reports for Court in Relation to Breastfeeding Infants and Young Children. Journal of Human Lactation. 2021. 37:683-688. doi:10.1177/0890334420975393. | Outcome
429 | Gribble, KD, Hausman, BL. Milk sharing and formula feeding: Infant feeding risks in comparative perspective?. Australas Med J. 2012. 5:275-83. doi:10.4066/amj.2012.1222. | Outcome
430 | Griffin, LB, Ding, JJ, Has, P, Ayala, N, Kole-White, MB. Lactation Consultation by an International Board Certified Lactation Consultant Improves Breastfeeding Rates for Mothers With Gestational Diabetes Mellitus. Journal of Human Lactation. 2022. 38:141-147. doi:10.1177/08903344211018622. | Independent variable - KQ2; Study participants
431 | Griswold, MK, Crawford, SL, Perry, DJ, Person, SD, Rosenberg, L, Cozier, YC, Palmer, JR. Experiences of Racism and Breastfeeding Initiation and Duration Among First-Time Mothers of the Black Women’s Health Study. J Racial Ethn Health Disparities. 2018. 5:1180-1191. doi:10.1007/s40615-018-0465-2. | Mediators/moderators; Intervention/exposure - KQ3
432 | Gross, RS, Mendelsohn, AL. Food Insecurity During Early Childhood: Marker for Disparities in Healthy Growth and Development. Pediatrics. 2019. 144:1-3. doi:10.1542/peds.2019-2430. | Outcome; Study design
433 | Gross, RS, Mendelsohn, AL, Fierman, AH, Hauser, NR, Messito, MJ. Maternal infant feeding behaviors and disparities in early child obesity. Child Obes. 2014. 10:145-52. doi:10.1089/chi.2013.0140. | Intervention/exposure - KQ3; Independent variable - KQ2
434 | Gross, RS, Mendelsohn, AL, Fierman, AH, Racine, AD, Messito, MJ. Food insecurity and obesogenic maternal infant feeding styles and practices in low-income families. Pediatrics. 2012. 130:254-61. doi:10.1542/peds.2011-3588. | Mediators/moderators; Intervention/exposure - KQ3
435 | Gross, SM, Orta-Aleman, D, Resnik, AK, Ducharme-Smith, K, Augustyn, M, Silbert-Flagg, J, Rosenblum, N, Caulfield, LE. Baby Friendly Hospital Designation and Breastfeeding Outcomes Among Maryland WIC Participants. Matern Child Health J. 2022. 26:1153-1159. doi:10.1007/s10995-022-03410-9. | Independent variable - KQ2; Study participants
436 | Gross, TT, Powell, R, Anderson, AK, Hall, J, Davis, M, Hilyard, K. WIC peer counselors’ perceptions of breastfeeding in African American women with lower incomes. J Hum Lact. 2015. 31:99-110. doi:10.1177/0890334414561061. | Data type; Study participants
437 | Grossman, X, Chaudhuri, J, Feldman-Winter, L, Abrams, J, Newton, KN, Philipp, BL, Merewood, A. Hospital Education in Lactation Practices (Project HELP): does clinician education affect breastfeeding initiation and exclusivity in the hospital?. Birth. 2009. 36:54-9. doi:10.1111/j.1523-536X.2008.00295.x. | Mediators/moderators; Study participants
438 | Grubesic, TH, Durbin, KM. A Spatial Analysis of Breastfeeding and Breastfeeding Support in the United States: The Leaders and Laggards Landscape. Journal of Human Lactation. 2019. 35:790-800. doi:10.1177/0890334419856615. | Independent variable - KQ2; Study participants
439 | Grubesic, TH, Durbin, KM. Breastfeeding Support: A Geographic Perspective on Access and Equity. J Hum Lact. 2017. 33:770-780. doi:10.1177/0890334417706361. | Study participants
440 | Grubesic, TH, Durbin, KM. Community Rates of Breastfeeding Initiation. J Hum Lact. 2016. 32:601-610. doi:10.1177/0890334416651070. | Mediators/moderators; Intervention/exposure - KQ3
441 | Grubesic, TH, Durbin, KM. Geodemographies of Breastfeeding Support. J Hum Lact. 2021. 37:301-313. doi:10.1177/0890334420941416. | Outcome
442 | Grubesic, TH, Durbin, KM. The complex geographies of telelactation and access to community breastfeeding support in the state of Ohio. PLoS One. 2020. 15:e0242457. doi:10.1371/journal.pone.0242457. | Outcome
443 | Grummer-Strawn, LM, Shealy, KR, Perrine, CG, Macgowan, C, Grossniklaus, DA, Scanlon, KS, Murphy, PE. Maternity Care Practices That Support Breastfeeding: CDC Efforts to Encourage Quality Improvement. Journal of Women’s Health (15409996). 2013. 22:107-112. doi:10.1089/jwh.2012.4158. | Independent variable - KQ2; Study participants
444 | Grummer-Strawn, LM, Shealy, KR. Progress in protecting, promoting, and supporting breastfeeding: 1984-2009. Breastfeed Med. 2009. 4 Suppl 1:S31-9. doi:10.1089/bfm.2009.0049. | Study design
445 | Gudger, K, Cartagena, D, Lowe, K. Program Evaluation of a Home Visiting Program: Perspectives of Home Visitors. Home Healthc Now. 2020. 38:311-317. doi:10.1097/nhh.0000000000000914. | Study participants
446 | Guendelman, S, Kosa, JL, Pearl, M, Graham, S, Goodman, J, Kharrazi, M. Juggling work and breastfeeding: effects of maternity leave and occupational characteristics. Pediatrics. 2009. 123:e38-46. doi:10.1542/peds.2008-2244. | Mediators/moderators; Study participants
447 | Guerra-Reyes, L, Christie, VM, Prabhakar, A, Harris, AL, Siek, KA. Postpartum Health Information Seeking Using Mobile Phones: Experiences of Low-Income Mothers. Matern Child Health J. 2016. 20:13-21. doi:10.1007/s10995-016-2185-8. | Intervention/exposure - KQ3; Independent variable - KQ2
448 | Gunderson, EP. The Role of Lactation in GDM Women. Clinical Obstetrics and Gynecology. 2013. 56:844-852. doi:10.1097/GRF.0b013e3182a8e067. | Study design
449 | Gupta, A, Meriwether, K, Hewlett, G. Impact of Training Specialty on Breastfeeding Among Resident Physicians: A National Survey. Breastfeed Med. 2019. 14:46-56. doi:10.1089/bfm.2018.0140. | Mediators/moderators; Intervention/exposure - KQ3
450 | Gurka, KK, Hornsby, PP, Drake, E, Mulvihill, EM, Kinsey, EN, Yitayew, MS, Lauer, C, Corriveau, S, Coleman, V, Gulati, G, Kellams, AL. Exploring intended infant feeding decisions among low-income women. Breastfeed Med. 2014. 9:377-84. doi:10.1089/bfm.2014.0013. | Outcome
451 | Gurley-Calvez, T, Bullinger, L, Kapinos, KA. Effect of the Affordable Care Act on Breastfeeding Outcomes. Am J Public Health. 2018. 108:277-283. doi:10.2105/ajph.2017.304108. | Mediators/moderators; Study participants
452 | Gypsy breastfeeding should be promoted. Nursing Times. 2012. 108:4-4. | Country; Study design
453 | Hackman, NM, Sznajder, KK, Kjerulff, KH. Paternal Education and Its Impact on Breastfeeding Initiation and Duration: An Understudied and Often Overlooked Factor in U.S. Breastfeeding Practices. Breastfeed Med. 2022. 17:429-436. doi:10.1089/bfm.2021.0338. | Mediators/moderators; Intervention/exposure - KQ3
454 | Haga, SM, Lynne, A, Slinning, K, Kraft, P. A qualitative study of depressive symptoms and well-being among first-time mothers. Scandinavian Journal of Caring Sciences. 2012. 26:458-466. doi:10.1111/j.1471-6712.2011.00950.x. | Country
455 | Haider, SJ, Chang, LV, Bolton, TA, Gold, JG, Olson, BH. An evaluation of the effects of a breastfeeding support program on health outcomes. Health Serv Res. 2014. 49:2017-34. doi:10.1111/1475-6773.12199. | Study participants
456 | Haile, ZT, Chavan, BB, Teweldeberhan, A, Chertok, IR. Association Between Gestational Weight Gain and Delayed Onset of Lactation: The Moderating Effects of Race/Ethnicity. Breastfeed Med. 2017. 12:79-85. doi:10.1089/bfm.2016.0134. | Outcome
457 | Hallowell, SGL. The associations between the nurse work environment, breastfeeding support and human milk provision in the NICU. University of Pennsylvania; 2013. | Publication status
458 | Hamad, R, Rehkopf, DH. Poverty, Pregnancy, and Birth Outcomes: A Study of the Earned Income Tax Credit. Paediatric and Perinatal Epidemiology. 2015. 29:444-452. doi:10.1111/ppe.12211. | Intervention/exposure - KQ3; Independent variable - KQ2; Study participants
459 | Hamdan, A, Tamim, H. The Relationship Between Postpartum Depression And Breastfeeding. International Journal of Psychiatry in Medicine. 2012. 43:243-259. doi:10.2190/PM.43.3.d. | Country
460 | Hamilton, AR, Tyson, MD, Braga, JA, Lerner, LB. Childbearing and pregnancy characteristics of female orthopaedic surgeons. J Bone Joint Surg Am. 2012. 94:e77. doi:10.2106/jbjs.K.00707. | Intervention/exposure - KQ3; Independent variable - KQ2
461 | Hamlin, L, Grunwald, L, Sturdivant, RX, Koehlmoos, TP. Comparison of Nurse-Midwife and Physician Birth Outcomes in the Military Health System. Policy Polit Nurs Pract. 2021. 22:105-113. doi:10.1177/1527154421994071. | Independent variable - KQ2; Study participants
462 | Hamner, HC, Beauregard, JL, Li, R, Nelson, JM, Perrine, CG. Meeting breastfeeding intentions differ by race/ethnicity, Infant and Toddler Feeding Practices Study-2. Matern Child Nutr. 2021. 17:e13093. doi:10.1111/mcn.13093. | Mediators/moderators; Intervention/exposure - KQ3
463 | Hamner, HC, Chiang, KV, Li, R. Returning to Work and Breastfeeding Duration at 12 Months, WIC Infant and Toddler Feeding Practices Study-2. Breastfeed Med. 2021. 16:956-964. doi:10.1089/bfm.2021.0081. | Mediators/moderators; Intervention/exposure - KQ3
464 | Hamner, HC, Perrine, CG, Gupta, PM, Herrick, KA, Cogswell, ME. Food Consumption Patterns among U.S. Children from Birth to 23 Months of Age, 2009-2014. Nutrients. 2017. 9:942. doi:10.3390/nu9090942. | Mediators/moderators; Intervention/exposure - KQ3
465 | Handa, D, Schanler, RJ. Role of the pediatrician in breastfeeding management. Pediatric Clinics of North America. 2013. 60:1-10. doi:10.1016/j.pcl.2012.10.004. | Study design
466 | Hannan, J, Brooten, D, Youngblut, JM, Galindo, AM. Comparing mothers’ postpartum concerns in two clinical trials 18 years apart. J Am Assoc Nurse Pract. 2016. 28:604-611. doi:10.1002/2327-6924.12384. | Mediators/moderators; Intervention/exposure - KQ3; Outcome
467 | Hardison-Moody, A, MacNell, L, Elliott, S, Bowen, S. How Social, Cultural, and Economic Environments Shape Infant Feeding for Low-Income Women: A Qualitative Study in North Carolina. J Acad Nutr Diet. 2018. 118:1886-1894.e1. doi:10.1016/j.jand.2018.01.008. | Intervention/exposure - KQ3; Independent variable - KQ2
468 | Harrington, SG, Wood, M, Porter, KK, Gupta, Y, Esfahani, SA, Daye, D, Kilcoyne, A, Donelan, K, Narayan, AK. Promoting Lactation Support: Challenges and Solutions to Supporting Breastfeeding Radiologists. Acad Radiol. 2022. 29:175-180. doi:10.1016/j.acra.2020.11.009. | Independent variable - KQ2; Study participants
469 | Harris, DE, Aboueissa, AM, Baugh, N, Sarton, C, Lichter, E. 11-year trends in pregnancy-related health indicators in Maine, 2000-2010. J Pregnancy. 2014. 2014:780626. doi:10.1155/2014/780626. | Intervention/exposure - KQ3; Independent variable - KQ2
470 | Harris, DE, Aboueissa, AM, Baugh, N, Sarton, C. Impact of rurality on maternal and infant health indicators and outcomes in Maine. Rural Remote Health. 2015. 15:3278. | Mediators/moderators; Intervention/exposure - KQ3
471 | Hassert, S, Kurpius, SER. Latinas and Postpartum Depression: Role of Partner Relationship, Additional Children, and Breastfeeding. Journal of Multicultural Counseling and Development. 2011. 39:90-100. doi:10.1002/j.2161-1912.2011.tb00143.x. | Outcome
472 | Hauck, K, Miraldo, M, Singh, S. Integrating motherhood and employment: A 22-year analysis investigating impacts of US workplace breastfeeding policy. SSM Popul Health. 2020. 11:100580. doi:10.1016/j.ssmph.2020.100580. | Study participants
473 | Hawkins, SS, Dow-Fleisner, S, Noble, A. Breastfeeding and the Affordable Care Act. Pediatric Clinics of North America. 2015. 62:1071-+. doi:10.1016/j.pcl.2015.05.002. | Study design; Study participants
474 | Hawkins, SS, Horvath, K, Noble, A, Baum, CF. ACA and Medicaid Expansion Increased Breast Pump Claims and Breastfeeding for Women with Public and Private Insurance. Womens Health Issues. 2022. 32:114-121. doi:10.1016/j.whi.2021.10.005. | Independent variable - KQ2; Study participants
475 | Hawkins, SS, Stern, AD, Baum, CF, Gillman, MW. Compliance with the Baby-Friendly Hospital Initiative and impact on breastfeeding rates. Arch Dis Child Fetal Neonatal Ed. 2014. 99:F138-43. doi:10.1136/archdischild-2013-304842. | Independent variable - KQ2; Study participants
476 | Hawkins, SS, Stern, AD, Baum, CF, Gillman, MW. Evaluating the impact of the Baby-Friendly Hospital Initiative on breast-feeding rates: a multi-state analysis. Public Health Nutr. 2015. 18:189-97. doi:10.1017/s1368980014000238. | Mediators/moderators; Study participants
477 | Hayashi, Y, Fisher, NM, Hantula, DA, Furman, L, Washio, Y. A behavioral economic demand analysis of mothers’ decision to exclusively breastfeed in the workplace. J Exp Anal Behav. 2022. 118:132-47. doi:10.1002/jeab.772. | Outcome; Study participants
478 | Hayes, DK, Boundy, EO, Hansen-Smith, H, Melcher, CL. Maternal Race Trends in Early Infant Feeding Patterns in Hawai’i Using Newborn Metabolic Screening-Birth Certificate Linked Data 2008-2015. Hawaii J Health Soc Welf. 2020. 79:42-50. | Mediators/moderators; Intervention/exposure - KQ3
479 | Hebert, S, Perry, L. P115 Breastfeeding Peer Counselors: Support Mothers Can Trust…Society for Nutrition Education and Behavior, 53rd Annual Conference, Virtual Conference, July 20-24, 2020. Journal of Nutrition Education & Behavior. 2020. 52:S70-S71. doi:10.1016/j.jneb.2020.04.162. | Publication status
480 | Heinig, MJ, Ishii, KD, Bañuelos, JL, Campbell, E, O’Loughlin, C, Vera Becerra, LE. Sources and acceptance of infant-feeding advice among low-income women. J Hum Lact. 2009. 25:163-72. doi:10.1177/0890334408329438. | Outcome
481 | Hellwig, JP. Supporting breastfeeding: Surgeon General’s call to action. Nurs Womens Health. 2011. 15:176-8. doi:10.1111/j.1751-486X.2011.01627.x. | Outcome; Study design
482 | Henderson, J, Gao, H, Redshaw, M. Experiencing maternity care: the care received and perceptions of women from different ethnic groups. BMC Pregnancy Childbirth. 2013. 13:196. doi:10.1186/1471-2393-13-196. | Country
483 | Hendrick, CE, Potter, JE. Nativity, Country of Education, and Mexican-Origin Women’s Breastfeeding Behaviors in the First 10 Months Postpartum. Birth. 2017. 44:68-77. doi:10.1111/birt.12261. | Mediators/moderators; Intervention/exposure - KQ3
484 | Hendricks, KM. Healthcare reform boosts breastfeeding. Breastfeeding Medicine. 2010. 5:265-268. doi:10.1089/bfm.2010.0063. | Outcome
485 | Henninger, ML, Irving, SA, Kauffman, TL, Kurosky, SK, Rompala, K, Thompson, MG, Sokolow, LZ, Avalos, LA, Ball, SW, Shifflett, P, Naleway, AL. Predictors of Breastfeeding Initiation and Maintenance in an Integrated Healthcare Setting. J Hum Lact. 2017. 33:256-266. doi:10.1177/0890334417695202. | Mediators/moderators; Intervention/exposure - KQ3
486 | Henry, LS, Christine Hansson, M, Haughton, VC, Waite, AL, Bowers, M, Siegrist, V, Thompson, EJ. Application of Kotter’s Theory of Change to Achieve Baby-Friendly Designation. Nurs Womens Health. 2017. 21:372-382. doi:10.1016/j.nwh.2017.07.007. | Study participants
487 | Henry-Moss, D, Abbuhl, S, Bellini, L, Spatz, DL. Lactation Space Experiences and Preferences Among Health Care Workers in an Academic Medical Center. Breastfeed Med. 2018. 13:607-613. doi:10.1089/bfm.2018.0101. | Intervention/exposure - KQ3; Independent variable - KQ2; Study participants
488 | Hensel, D, Helou, NE, Zhang, F, Stout, MJ, Raghuraman, N, Friedman, H, Carter, E, Odibo, AO, Kelly, JC. The Impact of a Multidisciplinary Opioid Use Disorder Prenatal Clinic on Breastfeeding Rates and Postpartum Care. Am J Perinatol. 2022. doi:10.1055/s-0042-1748526. | Mediators/moderators; Intervention/exposure - KQ3; Study participants
489 | Héon, M, Goulet, C, Garofalo, C, Nuyt, AM, Levy, E. An Intervention to Promote Breast Milk Production in Mothers of Preterm Infants. Western Journal of Nursing Research. 2016. 38:529-552. doi:10.1177/0193945914557501. | Country
490 | Hernandez, AR, Victora, CG. Biopolitics for breastfeeding: an analysis of the global and local movements and their links to social development discourses. Cadernos De Saude Publica. 2018. 34:12. doi:10.1590/0102-311x00155117. | Language
491 | Hernandez, IF. Acculturation, Self-Efficacy and Breastfeeding Behavior in a Sample of Hispanic Women. University of South Florida; 2014. | Publication status
492 | Hernández-Cordero, S, Pérez-Escamilla, R, Zambrano, P, Michaud-Létourneau, I, Lara-Mejía, V, Franco-Lares, B. Countries’ experiences scaling up national breastfeeding, protection, promotion and support programmes: Comparative case studies analysis. Matern Child Nutr. 2022. 18 Suppl 3:e13358. doi:10.1111/mcn.13358. | Independent variable - KQ2; Study participants
493 | Herold, RA, Bonuck, K. Medicaid IBCLC Service Coverage following the Affordable Care Act and the Center for Medicare and Medicaid Services Update. J Hum Lact. 2016. 32:89-94. doi:10.1177/0890334415599164. | Mediators/moderators; Study participants
494 | Hetherington, E, Tough, S, McNeil, D, Bayrampour, H, Metcalfe, A. Vulnerable Women’s Perceptions of Individual Versus Group Prenatal Care: Results of a Cross-Sectional Survey. Matern Child Health J. 2018. 22:1632-1638. doi:10.1007/s10995-018-2559-1. | Country
495 | HHS Promotes Breastfeeding Among African American Women. Inside Childbirth Education. 2013. 6-6. | Outcome
496 | Hildebrand, DA, McCarthy, P, Tipton, D, Merriman, C, Schrank, M, Newport, M. Innovative use of influential prenatal counseling may improve breastfeeding initiation rates among WIC participants. J Nutr Educ Behav. 2014. 46:458-66. doi:10.1016/j.jneb.2014.05.005. | Mediators/moderators; Study participants
497 | Hill, I, Courtot, B, Benatar, S, Thornburgh, S, Cross-Barnet, C. What do women in Medicaid say about enhanced prenatal care? Findings from the national Strong Start evaluation. Birth: Issues in Perinatal Care. 2019. 46:244-252. doi:10.1111/birt.12431. | Outcome
498 | Hilliard, E, Brunt, A. Impact of an Infant Friendly Business Designation. Health Promot Pract. 2020. 21:642-653. doi:10.1177/1524839918807442. | Mediators/moderators; Study participants
499 | Hilliard, TK. A Black Woman’s Commentary on Breastfeeding. Breastfeeding Medicine. 2014. 9:349-351. doi:10.1089/bfm.2014.0074. | Study design
500 | Hinic, KA. The relationships among perceived stress, birth satisfaction, and breastfeeding self-efficacy in early postpartum women. Seton Hall University; 2015. | Publication status
501 | Hinson, TD, Skinner, AC, Spatz, DL. Subject Matter Experts Identify Health Equity Concerns in Breastfeeding for African American Women. J Perinat Neonatal Nurs. 2021. 35:160-168. doi:10.1097/jpn.0000000000000486. | Study participants
502 | Hoban, R, Bigger, H, Patel, AL, Rossman, B, Fogg, LF, Meier, P. Goals for Human Milk Feeding in Mothers of Very Low Birth Weight Infants: How Do Goals Change and Are They Achieved During the NICU Hospitalization?. Breastfeed Med. 2015. 10:305-11. doi:10.1089/bfm.2015.0047. | Mediators/moderators; Intervention/exposure - KQ3
503 | Hoban, R, Bowker, RM, Gross, ME, Patel, AL. Maternal production of milk for infants in the neonatal intensive care unit. Semin Perinatol. 2021. 45:151381. doi:10.1016/j.semperi.2020.151381. | Study design
504 | Hodges, EA, Johnson, SL, Hughes, SO, Hopkinson, JM, Butte, NF, Fisher, JO. Development of the responsiveness to child feeding cues scale. Appetite. 2013. 65:210-9. doi:10.1016/j.appet.2013.02.010. | Outcome
505 | Hoffman, ER, Bentley, ME, Hamer, RM, Hodges, EA, Ward, DS, Bulik, CM. A comparison of infant and toddler feeding practices of mothers with and without histories of eating disorders. Matern Child Nutr. 2014. 10:360-72. doi:10.1111/j.1740-8709.2012.00429.x. | Intervention/exposure - KQ3; Independent variable - KQ2
506 | Hogan, VK, Rowley, DL, Brooks, PE, Gonzalez-Nahm, SN, Berthiaume, R, Thompson, Y, Derige, D. Achieving Breastfeeding Equity: A Study of a National Breastfeeding Initiative. Breastfeed Med. 2018. 13:142-148. doi:10.1089/bfm.2017.0068. | Study participants
507 | Hohman, EE, Paul, IM, Birch, LL, Savage, JS. INSIGHT responsive parenting intervention is associated with healthier patterns of dietary exposures in infants. Obesity (Silver Spring). 2017. 25:185-191. doi:10.1002/oby.21705. | Outcome
508 | Holbrook, KE, White, MC, Heyman, MB, Wojcicki, JM. Maternal sociodemographic characteristics and the use of the Iowa Infant Attitude Feeding Scale to describe breastfeeding initiation and duration in a population of urban, Latina mothers: a prospective cohort study. Int Breastfeed J. 2013. 8:7. doi:10.1186/1746-4358-8-7. | Intervention/exposure - KQ3; Comparator - KQ2
509 | Holm, KG, Clemensen, J, Brødsgaard, A, Smith, AC, Maastrup, R, Zachariassen, G. Growth and breastfeeding of preterm infants receiving neonatal tele-homecare compared to hospital-based care. J Neonatal Perinatal Med. 2019. 12:277-284. doi:10.3233/npm-18143. | Country
510 | Holmes, AV, Chin, NP, Kaczorowski, J, Howard, CR. A barrier to exclusive breastfeeding for WIC enrollees: limited use of exclusive breastfeeding food package for mothers. Breastfeed Med. 2009. 4:25-30. doi:10.1089/bfm.2008.0110. | Intervention/exposure - KQ3; Independent variable - KQ2
511 | Holmquist, I, Pohnan, R, Stritecka, H, Spevakova, B, Vasek, T, Bostikova, V. Breastfeeding During Military Service: Different Countries, Different Possibilities. Mil Med. 2021. 186:537-542. doi:10.1093/milmed/usab016. | Study design
512 | Hornsby, PP, Gurka, KK, Conaway, MR, Kellams, AL. Reasons for Early Cessation of Breastfeeding Among Women with Low Income. Breastfeed Med. 2019. 14:375-381. doi:10.1089/bfm.2018.0206. | Intervention/exposure - KQ3; Independent variable - KQ2
513 | Horodynski, MA, Olson, B, Baker, S, Brophy-Herb, H, Auld, G, Van Egeren, L, Lindau, J, Singleterry, L. Healthy babies through infant-centered feeding protocol: an intervention targeting early childhood obesity in vulnerable populations. Bmc Public Health. 2011. 11:6. doi:10.1186/1471-2458-11-868. | Outcome; Other (Protocol)
514 | Hospital Working to Close Health Inequity Gaps. Neonatal Intensive Care. 2021. 34:56-59. | Outcome
515 | Houghtaling, B, Byker Shanks, C, Ahmed, S, Rink, E. Grandmother and health care professional breastfeeding perspectives provide opportunities for health promotion in an American Indian community. Soc Sci Med. 2018. 208:80-88. doi:10.1016/j.socscimed.2018.05.017. | Study participants
516 | Howard, TF, Hinten, B, Ott, CM, Ye, Y, Tita, ATN. What Women Really Think About Breastfeeding and Breast Pumping: A Qualitative Analysis of Women Who Deliver at a Baby-Friendly Hospital. Breastfeed Med. 2022. 17:65-71. doi:10.1089/bfm.2021.0135. | Mediators/moderators; Outcome
517 | Hoyt-Austin, A, Hazrati, S, Berlin, S, Hourigan, S, Bodnar, K. Association of Maternal Confidence and Breastfeeding Practices in Hispanic Women Compared to Non-Hispanic White Women. Glob Pediatr Health. 2021. 8:2333794x211062439. doi:10.1177/2333794x211062439. | Outcome
518 | Huang, R, Yang, M. Paid maternity leave and breastfeeding practice before and after California’s implementation of the nation’s first paid family leave program. Econ Hum Biol. 2015. 16:45-59. doi:10.1016/j.ehb.2013.12.009. | Mediators/moderators; Study participants
519 | Huang, Y, Hauck, FR, Signore, C, Yu, A, Raju, TN, Huang, TT, Fein, SB. Influence of bedsharing activity on breastfeeding duration among US mothers. JAMA Pediatr. 2013. 167:1038-44. doi:10.1001/jamapediatrics.2013.2632. | Mediators/moderators; Intervention/exposure - KQ3
520 | Hudak, KM, Benjamin-Neelon, SE. Timing of WIC Enrollment and Responsive Feeding among Low-Income Women in the US. Int J Environ Res Public Health. 2021. 18:7695. doi:10.3390/ijerph18147695. | Mediators/moderators; Intervention/exposure - KQ3
521 | Hudson, IJ, Rutledge, G, Roberts Ayers, D. A Case Study of Michigan’s Breastfeeding Initiative: The Role of Coalitions in Community-Based Breastfeeding Support. J Hum Lact. 2015. 31:611-3. doi:10.1177/0890334415601358. | Outcome
522 | Hundalani, SG, Irigoyen, M, Braitman, LE, Matam, R, Mandakovic-Falconi, S. Breastfeeding among inner-city women: from intention before delivery to breastfeeding at hospital discharge. Breastfeed Med. 2013. 8:68-72. doi:10.1089/bfm.2012.0004. | Mediators/moderators; Intervention/exposure - KQ3
523 | Hung, KJ, Berg, O. Early Skin-to-Skin After Cesarean to Improve Breastfeeding. MCN: The American Journal of Maternal Child Nursing. 2011. 36:318-326. doi:10.1097/NMC.0b013e3182266314. | Outcome
524 | Hunt, L, Thomson, G, Whittaker, K, Dykes, F. Adapting breastfeeding support in areas of socio-economic deprivation: a case study approach. Int J Equity Health. 2021. 20:83. doi:10.1186/s12939-021-01393-7. | Country
525 | Hunter, J. (Not) breastfeeding in the low-wage, non-union American workplace. Breastfeed Med. 2013. 8:445-7. doi:10.1089/bfm.2013.0074. | Study design
526 | Hussain, S, Lowell, GS, Roehler, DR, Quinlan, KP, Tandon, SD, Schwartz, L. You can have your breastmilk and safe sleep too: a preliminary analysis of infant safe sleep data in a Midwestern home visiting program. Inj Epidemiol. 2018. 5:14. doi:10.1186/s40621-018-0138-y. | Outcome
527 | Hwang, SS, Lu, E, Cui, X, Diop, H, Barfield, WD, Manning, SE. Home care practices for preterm and term infants after hospital discharge in Massachusetts, 2007 to 2010. J Perinatol. 2015. 35:880-4. doi:10.1038/jp.2015.90. | Mediators/moderators; Intervention/exposure - KQ3
528 | Hyden, Christel, Kahn, Richard, Bonuck, Karen. Bottle-Weaning Intervention Tools: The “How” and “Why” of a WIC-Based Educational Flipchart, Parent Brochure, and Website. Health Promotion Practice. 2013. 14:75-80. doi:10.1177/1524839910396364. | Outcome
529 | Hydery, T, Shields, S, Hen, E, Rizzo, P, Sullivan, K, Savageau, JA. The Impact of Local Education and Resource Distribution on Maternal Health Behaviors. Matern Child Health J. 2022. 26:1676-88. doi:10.1007/s10995-022-03416-3. | Outcome
530 | Ibarra-Ortega, A, Vásquez-Garibay, EM, Larrosa-Haro, A, Vizmanos-Lamotte, B, Castro-Albarrán, J. Factors associated with longer breastfeeding duration in Mexican working mothers. Aten Primaria. 2021. 53:102097. doi:10.1016/j.aprim.2021.102097. | Country
531 | Ikonen, R, Paavilainen, E, Helminen, M, Kaunonen, M. Preterm infants’ mothers’ initiation and frequency of breast milk expression and exclusive use of mother’s breast milk in neonatal intensive care units. J Clin Nurs. 2018. 27:e551-e558. doi:10.1111/jocn.14093. | Country
532 | Imboden, A, Lawson, R. Improving breastfeeding duration through creation of a breastfeeding-friendly pediatric practice. J Am Assoc Nurse Pract. 2021. 33:1273-1281. doi:10.1097/jxx.0000000000000521. | Independent variable - KQ2; Study participants
533 | Improving breastfeeding rates in the Hutt Valley. Kai Tiaki Nursing New Zealand. 2014. 20:9-9. | Country
534 | Insaf, TZ, Fortner, RT, Pekow, P, Dole, N, Markenson, G, Chasan-Taber, L. Prenatal stress, anxiety, and depressive symptoms as predictors of intention to breastfeed among Hispanic women. J Womens Health (Larchmt). 2011. 20:1183-92. doi:10.1089/jwh.2010.2276. | Intervention/exposure - KQ3; Outcome; Comparator - KQ2
535 | INSTRUCTIONS: Subject Matter Experts Identify Health Equity Concerns in Breastfeeding for African American Women. J Perinat Neonatal Nurs. 2021. 35:E10. doi:10.1097/jpn.0000000000000575. | Study design
536 | Iyengar, AS, Ein-Dor, T, Zhang, EX, Chan, SJ, Kaimal, AJ, Dekel, S. Increased traumatic childbirth and postpartum depression and lack of exclusive breastfeeding in Black and Latinx individuals. International Journal of Gynecology & Obstetrics. 2022. doi:10.1002/ijgo.14280. | Mediators/moderators; Intervention/exposure - KQ3
537 | Jackson, DB, Johnson, KR. Does breast-feeding reduce offspring junk food consumption during childhood? Examinations by socio-economic status and race/ethnicity. Public Health Nutr. 2017. 20:1441-1451. doi:10.1017/s1368980016003517. | Mediators/moderators; Intervention/exposure - KQ3
538 | Jacob, S, Byrne, M, Keenan, K. Neonatal Physiological Regulation is Associated With Perinatal Factors: A Study of Neonates Born to Healthy African American Women Living In Poverty. Infant Ment Health J. 2009. 30:82-94. doi:10.1002/imhj.20204. | Outcome
539 | Jacobson, A. Focus on Fathers for Promoting Safe Sleep and Breastfeeding. Neonatology Today. 2021. 16:50-51. doi:10.51362/neonatology.today/202171675051. | Outcome
540 | Jacobson, LT, Zackula, R, Redmond, ML, Duong, J, Collins, TC. Pioneer baby: suggestions for pre- and postnatal health promotion programs from rural English and Spanish-speaking pregnant and postpartum women. J Behav Med. 2018. 41:653-667. doi:10.1007/s10865-018-9930-y. | Study participants
541 | Jacobson, LT, Zackula, RE, Lu, K. Effectiveness of a Pilot Breastfeeding Educational Intervention Targeting High BMI Pregnant Women. Kans J Med. 2020. 13:219-227. | Mediators/moderators; Outcome; Study participants
542 | Jain, S, Neaves, S, Royston, A, Huang, I, Juengst, SB. Breastmilk pumping experiences of physician mothers: quantitative and qualitative findings from a nationwide survey study. J Gen Intern Med. 2022. 37:3411-8. doi:10.1007/s11606-021-07388-y. | Independent variable - KQ2; Study participants
543 | Janevic, T, Maru, S, Nowlin, S, McCarthy, K, Bergink, V, Stone, J, Dias, J, Wu, S, Howell, EA. Pandemic Birthing: Childbirth Satisfaction, Perceived Health Care Bias, and Postpartum Health During the COVID-19 Pandemic. Matern Child Health J. 2021. 25:860-869. doi:10.1007/s10995-021-03158-8. | Mediators/moderators; Intervention/exposure - KQ3; Study participants
544 | Jantzer, AM, Anderson, J, Kuehl, RA. Breastfeeding Support in the Workplace: The Relationships Among Breastfeeding Support, Work-Life Balance, and Job Satisfaction. J Hum Lact. 2018. 34:379-385. doi:10.1177/0890334417707956. | Outcome
545 | Jaywant, SS, Patil, SS, Shrivastav, DS. To Analyze the Effect of Person-Environment-Occupation Intervention Model on Stress and Breast-Feeding Efficacy on Mothers of Preterm Neonates: A Randomized Controlled Study. Indian Journal of Occupational Therapy (Wolters Kluwer India Pvt Ltd). 2020. 52:24-29. doi:10.4103/ijoth.ijoth_1_20. | Country
546 | Jefferson, UT, Bloom, TL. Determinants of Breastfeeding Behavior Among African American Women. JOGNN: Journal of Obstetric, Gynecologic & Neonatal Nursing. 2016. 45:S44-S44. doi:10.1016/j.jogn.2016.03.112. | Publication status
547 | Jefferson, UT. Attitudes, subjective norms, and intentions regarding infant feeding methods among Black college students. Saint Louis University; 2012. | Study participants
548 | Jefferson, UT. Breastfeeding Exposure, Attitudes, and Intentions of African American and Caucasian College Students. J Hum Lact. 2017. 33:149-156. doi:10.1177/0890334416679384. | Study participants
549 | Jefferson, UT. Infant feeding attitudes and breastfeeding intentions of black college students. West J Nurs Res. 2014. 36:1338-56. doi:10.1177/0193945913514638. | Study participants
550 | Jensen, E, Labbok, M. Unintended consequences of the WIC formula rebate program on infant feeding outcomes: will the new food packages be enough?. Breastfeed Med. 2011. 6:145-9. doi:10.1089/bfm.2010.0022. | Study design
551 | Jensen, E. Participation in the Supplemental Nutrition Program for Women, Infants and Children (WIC) and breastfeeding: national, regional, and state level analyses. Matern Child Health J. 2012. 16:624-31. doi:10.1007/s10995-011-0796-7. | Mediators/moderators; Intervention/exposure - KQ3; Study participants
552 | Jiang, B, Hua, J, Wang, Y, Fu, Y, Zhuang, Z, Zhu, L. Evaluation of the impact of breast milk expression in early postpartum period on breastfeeding duration: a prospective cohort study. BMC Pregnancy Childbirth. 2015. 15:268. doi:10.1186/s12884-015-0698-6. | Country
553 | Jiang, L, Li, X, Wang, MC, Osgood, N, Whaley, SE, Crespi, CM. Estimating the population impact of hypothetical breastfeeding interventions in a low-income population in Los Angeles County: An agent-based model. PLoS One. 2020. 15:e0231134. doi:10.1371/journal.pone.0231134. | Study design
554 | Jiang, M, Foster, EM, Gibson-Davis, CM. The effect of WIC on breastfeeding: A new look at an established relationship. Children and Youth Services Review. 2010. 32:264-273. doi:10.1016/j.childyouth.2009.09.005. | Mediators/moderators; Study participants
555 | Johnson, AM, Correll, A, Greene, JF, Hein, D, McLaughlin, T. Barriers to breastfeeding in a resident clinic. Breastfeed Med. 2013. 8:273-6. doi:10.1089/bfm.2012.0020. | Intervention/exposure - KQ3; Independent variable - KQ2
556 | Johnson, AM, Menke, R, Handelzalts, JE, Green, K, Muzik, M. Reimagining Racial Trauma as a Barrier to Breastfeeding Versus Childhood Trauma and Depression Among African American Mothers. Breastfeed Med. 2021. 16:493-500. doi:10.1089/bfm.2020.0304. | Mediators/moderators; Intervention/exposure - KQ3
557 | Johnson, B, Gargiullo, P, Murphy, TV, Parashar, UD, Patel, MM. Sociodemographic and dietary risk factors for natural infant intussusception in the United States. J Pediatr Gastroenterol Nutr. 2010. 51:458-63. doi:10.1097/MPG.0b013e3181d3273f. | Outcome
558 | Johnson, DB, Lamson, E, Schwartz, R, Goldhammer, C, Ellings, A. A Community Health Clinic Breastfeeding-Friendly Pilot: What Can We Learn about the Policy Process?. J Hum Lact. 2015. 31:660-70. doi:10.1177/0890334415579656. | Outcome
559 | Johnson, EL, Burke, AE, Wang, A, Pennell, PB. Unintended pregnancy, prenatal care, newborn outcomes, and breastfeeding in women with epilepsy. Neurology. 2018. 91:e1031-e1039. doi:10.1212/wnl.0000000000006173. | Mediators/moderators; Intervention/exposure - KQ3
560 | Johnson, G, Levison, J, Malek, J. Should Providers Discuss Breastfeeding With Women Living With HIV in High-Income Countries? An Ethical Analysis. Clin Infect Dis. 2016. 63:1368-1372. doi:10.1093/cid/ciw587. | Study design
561 | Johnson, HM, Mitchell, KB, Snyder, RA. Call to Action: Universal Policy to Support Residents and Fellows Who Are Breastfeeding. J Grad Med Educ. 2019. 11:382-384. doi:10.4300/jgme-d-19-00140.1. | Outcome; Study design
562 | Johnson, KV, Scott, AL, Shreve, M, Ayers, BL, Seaton, VS, McElfish, PA. Marshallese Beliefs, Perceptions, and Practices Related to Child Feeding Among Marshallese in the United States: Implications for Childhood Obesity. Nutr Metab Insights. 2019. 12:1178638819827609. doi:10.1177/1178638819827609. | Intervention/exposure - KQ3; Study participants
563 | Johnson, Sally, Leeming, Dawn, Williamson, Iain, Lyttle, Steven. Maintaining the ‘good maternal body’: expressing milk as a way of negotiating the demands and dilemmas of early infant feeding. Journal of Advanced Nursing (John Wiley & Sons, Inc.). 2013. 69:590-599. doi:10.1111/j.1365-2648.2012.06035.x. | Country
564 | Jolles, DR, Langford, R, Stapleton, S, Cesario, S, Koci, A, Alliman, J. Outcomes of childbearing Medicaid beneficiaries engaged in care at Strong Start birth center sites between 2012 and 2014. Birth. 2017. 44:298-305. doi:10.1111/birt.12302. | Outcome
565 | Jones, A, Reller, L, Knowles, J, Lin, FC, Lohr, J. Decisions Regarding Newborn Feeding by Latina Mothers. Clin Pediatr (Phila). 2018. 57:168-172. doi:10.1177/0009922817692317. | Mediators/moderators; Intervention/exposure - KQ3
566 | Jones, E, Emmett, C, Spencer, SA. An evaluation of preterm breastfeeding information and support. Infant. 2009. 5:116-120. | Country
567 | Jones, E. The impact of exhaustion on Step 6 of the Baby Friendly Initiative. British Journal of Midwifery. 2011. 19:483-488. | Country; Study participants
568 | Jones, JD. Postpartum Mothers’ Attitudes Toward Breastfeeding. Walden University; 2017. | Publication status
569 | Jones, JR, Kogan, MD, Singh, GK, Dee, DL, Grummer-Strawn, LM. Factors associated with exclusive breastfeeding in the United States. Pediatrics. 2011. 128:1117-25. doi:10.1542/peds.2011-0841. | Mediators/moderators; Intervention/exposure - KQ3
570 | Jones, LB, Mallin, EA. Dr. MILK: support program for physician mothers. Breastfeed Med. 2013. 8:330-2. doi:10.1089/bfm.2013.0037. | Independent variable - KQ2; Outcome; Study participants
571 | Jordan, S, Davies, GI, Thayer, DS, Tucker, D, Humphreys, I. Antidepressant prescriptions, discontinuation, depression and perinatal outcomes, including breastfeeding: A population cohort analysis. PLoS One. 2019. 14:e0225133. doi:10.1371/journal.pone.0225133. | Country
572 | Joseph, HM, Emery, RL, Bogen, DL, Levine, MD. The Influence of Smoking on Breast feeding Among Women Who Quit Smoking During Pregnancy. Nicotine Tob Res. 2017. 19:652-655. doi:10.1093/ntr/ntw254. | Mediators/moderators; Intervention/exposure - KQ3
573 | Joshi, A, Amadi, C, Meza, J, Aguire, T, Wilhelm, S. Evaluation of a computer-based bilingual breastfeeding educational program on breastfeeding knowledge, self-efficacy and intent to breastfeed among rural Hispanic women. Int J Med Inform. 2016. 91:10-9. doi:10.1016/j.ijmedinf.2016.04.001. | Outcome
574 | Joshi, A, Amadi, C, Meza, J, Aguirre, T, Wilhelm, S. Comparison of Socio-Demographic Characteristics of a Computer Based Breastfeeding Educational Intervention Among Rural Hispanic Women. J Community Health. 2015. 40:993-1001. doi:10.1007/s10900-015-0023-3. | Outcome
575 | Joshi, A, Perin, DM, Amadi, C, Trout, K. Evaluating the usability of an interactive, bi-lingual, touchscreen-enabled breastfeeding educational programme: application of Nielson’s heuristics. J Innov Health Inform. 2015. 22:265-74. doi:10.14236/jhi.v22i2.71. | Outcome
576 | Joshi, A, Wilhelm, S, Aguirre, T, Trout, K, Amadi, C. An interactive, bilingual touch screen program to promote breastfeeding among Hispanic rural women: usability study. JMIR Res Protoc. 2013. 2:e47. doi:10.2196/resprot.2872. | Outcome
577 | Joyce, T, Reeder, J. Changes in breastfeeding among WIC participants following implementation of the new food package. Matern Child Health J. 2015. 19:868-76. doi:10.1007/s10995-014-1588-7. | Mediators/moderators; Intervention/exposure - KQ3
578 | K, M, Chowdary, S, Masthi, R. Breast feeding practices and newborn care in rural areas: a descriptive cross-sectional study. Indian Journal of Community Medicine. 2009. 34:243-246. doi:10.4103/0970-0218.55292. | Country
579 | Kacica, MA, Kreiger, L, Johnson, GD. Breastfeeding practices in New York State maternity hospitals: results from a statewide survey. Breastfeed Med. 2012. 7:409-16. doi:10.1089/bfm.2011.0149. | Independent variable - KQ2; Study participants
580 | Kaikini, KL, Hyrkas, K. Mothers’ Intentions to Breastfeed and Hospital Practices on Breastfeeding: A Longitudinal Study at 6 Months After Birth on Predictors of Breastfeeding in a Cohort of Mothers From a Large Northern New England Medical Center. JOGNN: Journal of Obstetric, Gynecologic & Neonatal Nursing. 2014. 43:S78-S78. doi:10.1111/1552-6909.12458. | Publication status
581 | Kair, LR, Flaherman, VJ. Donor Milk or Formula: A Qualitative Study of Postpartum Mothers of Healthy Newborns. Journal of Human Lactation. 2017. 33:710-716. doi:10.1177/0890334417716417. | Intervention/exposure - KQ3; Independent variable - KQ2
582 | Kair, LR, Colaizy, TT. Breastfeeding Continuation Among Late Preterm Infants: Barriers, Facilitators, and Any Association With NICU Admission?. Hosp Pediatr. 2016. 6:261-8. doi:10.1542/hpeds.2015-0172. | Mediators/moderators; Intervention/exposure - KQ3
583 | Kair, LR, Nidey, NL, Marks, JE, Hanrahan, K, Femino, L, Fernandez, YGE, Ryckman, K, Wood, KE. Disparities in Donor Human Milk Supplementation Among Well Newborns. J Hum Lact. 2020. 36:74-80. doi:10.1177/0890334419888163. | Outcome
584 | Kallem, S, Gruver, RS, Virudachalam, S, Fiks, AG. Mothers’ Facebook posts about infant health: findings from the Grow2Gether study. BMC Pediatr. 2018. 18:341. doi:10.1186/s12887-018-1315-4. | Outcome
585 | Kalluri, NS, Burnham, LA, Lopera, AM, Stickney, DM, Combs, GL, Levesque, BM, Philipp, BL, Parker, MG. A Quality Improvement Project to Increase Mother’s Milk Use in an Inner-City NICU. Pediatr Qual Saf. 2019. 4:e204. doi:10.1097/pq9.0000000000000204. | Outcome
586 | Kamoun, C, Spatz, D. Influence of Islamic Traditions on Breastfeeding Beliefs and Practices Among African American Muslims in West Philadelphia: A Mixed-Methods Study. J Hum Lact. 2018. 34:164-175. doi:10.1177/0890334417705856. | Outcome
587 | Kapinos, K, Kotzias, V, Bogen, D, Ray, K, Demirci, J, Rigas, MA, Uscher-Pines, L. The Use of and Experiences With Telelactation Among Rural Breastfeeding Mothers: Secondary Analysis of a Randomized Controlled Trial. J Med Internet Res. 2019. 21:e13967. doi:10.2196/13967. | Independent variable - KQ2; Study participants
588 | Kaplan, DL. Making breastfeeding the norm in New York City. Breastfeed Med. 2010. 5:211-2. doi:10.1089/bfm.2010.0042. | Outcome
589 | Karall, D, Ndayisaba, JP, Heichlinger, A, Kiechl-Kohlendorfer, U, Stojakovic, S, Leitner, H, Scholl-Bürgi, S. Breast-feeding Duration: Early Weaning-Do We Sufficiently Consider the Risk Factors?. J Pediatr Gastroenterol Nutr. 2015. 61:577-82. doi:10.1097/mpg.0000000000000873. | Country
590 | Karanja, N, Lutz, T, Ritenbaugh, C, Maupome, G, Jones, J, Becker, T, Aickin, M. The TOTS community intervention to prevent overweight in American Indian toddlers beginning at birth: a feasibility and efficacy study. J Community Health. 2010. 35:667-75. doi:10.1007/s10900-010-9270-5. | Comparator
591 | Karbandi, S, Hosseini, SM, Hosseini, SA, Sadeghi, F, Hesari, M, Masoudi, R. Evaluating the Effectiveness of Using a Progressive Muscle Relaxation Technique on the Self-Efficacy of Breastfeeding in Mothers With Preterm Infants. J Nurs Res. 2017. 25:283-288. doi:10.1097/jnr.0000000000000217. | Country
592 | Karmaus, Wilfried, Soto-Ramírez, Nelís, Hongmei, Zhang. Infant feeding pattern in the first six months of age in USA: a follow-up study. International Breastfeeding Journal. 2017. 12:1-11. doi:10.1186/s13006-017-0139-4. | Mediators/moderators; Intervention/exposure - KQ3
593 | Karol, SV. IHS and the baby-friendly hospital initiative. Breastfeed Med. 2014. 9:347-8. doi:10.1089/bfm.2014.0102. | Outcome
594 | Karp, SM, Howe-Heyman, A, Dietrich, MS, Lutenbacher, M. Breastfeeding initiation in the context of a home intervention to promote better birth outcomes. Breastfeed Med. 2013. 8:381-7. doi:10.1089/bfm.2012.0151. | Mediators/moderators; Study participants
595 | Karp, SM, Lutenbacher, M. Infant feeding practices of young mothers. MCN Am J Matern Child Nurs. 2011. 36:98-103. doi:10.1097/NMC.0b013e31820558bf. | Mediators/moderators; Intervention/exposure - KQ3
596 | Kassierer, MY, O’Connor, DL, Rutherford, E, Rolnitzky, A, Unger, S. Implications for Observant Jewish Families in the Provision of Mother’s Own and Donor Milk for Their Very Low Birth Weight Infant. Journal of Human Lactation. 2014. 30:402-404. doi:10.1177/0890334414545538. | Study design
597 | Kavanagh, KF, Habibi, M, Anderson, K, Spence, M. Caregiver- vs infant-oriented feeding: a model of infant-feeding strategies among special supplemental nutrition program for women, infants, and children participants in rural east Tennessee. J Am Diet Assoc. 2010. 110:1485-91. doi:10.1016/j.jada.2010.07.009. | Independent variable - KQ2; Study participants
598 | Kawamura, MY, Kimata, C, Wong Ramsey, K. Racial Disparities in Breastmilk Receipt and Extremely Low Gestational Age Neonatal Morbidities in an Asian Pacific Islander Population. J Racial Ethn Health Disparities. 2022. doi:10.1007/s40615-022-01283-w. | Mediators/moderators; Intervention/exposure - KQ3
599 | Kay, MC, Cholera, R, Flower, KB, Yin, HS, Rothman, RL, Sanders, LM, Delamater, AM, Perrin, EM. Are Low-Income, Diverse Mothers Able to Meet Breastfeeding Intentions After 2 Months of Breastfeeding?. Breastfeed Med. 2020. 15:435-442. doi:10.1089/bfm.2020.0025. | Mediators/moderators; Intervention/exposure - KQ3
600 | Keddem, S, Frasso, R, Dichter, M, Hanlon, A. The Association Between Pregnancy Intention and Breastfeeding. J Hum Lact. 2018. 34:97-105. doi:10.1177/0890334417725032. | Mediators/moderators; Intervention/exposure - KQ3
601 | Keddem, S, Solomon, P, Marcus, SC, Schapira, MM, Mattocks, KM. Disparities in Breastfeeding Among Military Veterans. J Hum Lact. 2020. 36:64-73. doi:10.1177/0890334419888200. | Mediators/moderators; Intervention/exposure - KQ3
602 | Kedia, SK, Ahuja, NA, Carswell, A, Vander Weg, MW, Scarinci, IC, Ward, KD. Smoking Cessation among Pregnant and Postpartum Women from Low-Income Groups in the United States. J Midwifery Womens Health. 2021. 66:486-493. doi:10.1111/jmwh.13242. | Country
603 | Keenan-Devlin, L, Smart, BP, Stamos, G, Hughes-Jones, J, Borders, A. 534: Reducing racial disparities in breastfeeding with the implementation of a breastfeeding peer counselor program. American Journal of Obstetrics & Gynecology. 2020. 222:S344-S345. doi:10.1016/j.ajog.2019.11.550. | Publication status
604 | Keenan-Devlin, LS, Awosemusi, YF, Grobman, W, Simhan, H, Adam, E, Culhane, J, Miller, G, Borders, AEB. Early Term Delivery and Breastfeeding Outcomes. Matern Child Health J. 2019. 23:1339-1347. doi:10.1007/s10995-019-02787-4. | Mediators/moderators; Study participants
605 | Keim, SA, Boone, KM, Oza-Frank, R, Geraghty, SR. Pumping Milk Without Ever Feeding at the Breast in the Moms2Moms Study. Breastfeeding Medicine. 2017. 12:422-429. doi:10.1089/bfm.2017.0025. | Independent variable - KQ2; Study participants
606 | Keim, SA, McNamara, KA, Dillon, CE, Strafford, K, Ronau, R, McKenzie, LB, Geraghty, SR. Breastmilk sharing: awareness and participation among women in the Moms2Moms Study. Breastfeeding Medicine. 2014. 9:398-406. doi:10.1089/bfm.2014.0032. | Outcome
607 | Keim, SA, Smith, K, Ingol, T, Rui, L, Boone, KM, Oza-Frank, R, Li, R. Improved Estimation of Breastfeeding Rates Using a Novel Breastfeeding and Milk Expression Survey. Breastfeeding Medicine. 2019. 14:499-507. doi:10.1089/bfm.2018.0258. | Mediators/moderators; Intervention/exposure - KQ3
608 | Keitt, SH, Reis-Reilly, H, Fuller-Sankofa, N, Carr, M. Breastfeeding in the Community: Sharing Stories on Implementations That Work. Journal of Human Lactation. 2018. 34:285-303. doi:10.1177/0890334418757957. | Mediators/moderators; Comparator - KQ3
609 | Kellams, A, Hauck, FR, Moon, RY, Kerr, SM, Heeren, T, Corwin, MJ, Colson, E. Factors Associated With Choice of Infant Sleep Location. Pediatrics. 2020. 145: e20191523. doi:10.1542/peds.2019-1523. | Outcome
610 | Kellams, A, Kerr, SM, Moon, RY, Hauck, FR, Heeren, T, Colson, E, Parker, MG, Rice, F, Corwin, MJ. The Impact of Breastfeeding and Safe Sleep Mobile Health Messaging on Breastfeeding and Bedsharing. Acad Pediatr. 2022. 22:927-34. doi:10.1016/j.acap.2022.01.016. | Mediators/moderators; Study participants
611 | Kellams, AL, Gurka, KK, Hornsby, PP, Drake, E, Conaway, MR. A Randomized Trial of Prenatal Video Education to Improve Breastfeeding Among Low-Income Women. Breastfeed Med. 2018. 13:666-673. doi:10.1089/bfm.2018.0115. | Mediators/moderators; Study participants
612 | Kellams, AL, Gurka, KK, Hornsby, PP, Drake, E, Riffon, M, Gellerson, D, Gulati, G, Coleman, V. The Impact of a Prenatal Education Video on Rates of Breastfeeding Initiation and Exclusivity during the Newborn Hospital Stay in a Low-income Population. J Hum Lact. 2016. 32:152-9. doi:10.1177/0890334415599402. | Mediators/moderators; Study participants
613 | Kendzor, DE, Businelle, MS, Costello, TJ, Castro, Y, Reitzel, LR, Vidrine, JI, Li, Y, Mullen, PD, Velasquez, MM, Cinciripini, PM, Cofta-Woerpel, LM, Wetter, DW. Breast feeding is associated with postpartum smoking abstinence among women who quit smoking due to pregnancy. Nicotine Tob Res. 2010. 12:983-8. doi:10.1093/ntr/ntq132. | Mediators/moderators; Intervention/exposure - KQ3
614 | Khasawneh, W. Breastfeeding Practices, Facilitators, and Barriers among Immigrant Muslim Arab Women Living in a Metropolitan Area of the Southwest of United States. Arizona State University; 2017. | Publication status
615 | Kim, E, Hoetmer, SE, Li, Y, Vandenberg, JE. Relationship between intention to supplement with infant formula and breastfeeding duration. Can J Public Health. 2013. 104:e388-93. doi:10.17269/cjph.104.3898. | Country
616 | Kim, J, Gallien, TL. Childcare arrangements and infant feeding practices by family structure and household income among US children aged 0 to 2 years. Matern Child Nutr. 2016. 12:591-602. doi:10.1111/mcn.12152. | Intervention/exposure - KQ3; Independent variable - KQ2
617 | Kim, J, Mathai, RA. Comparison of Feeding Practices in Infants in the WIC Supplemental Nutrition Program Who Were Enrolled in Child Care as Opposed to Those with Parent Care Only. Breastfeed Med. 2015. 10:371-6. doi:10.1089/bfm.2014.0179. | Independent variable - KQ2; Study participants
618 | Kim, J, Shim, JE. Response: Breastfeeding Duration in Relation to Child Care and Participation in WIC. Journal of Human Lactation. 2012. 28:414-415. doi:10.1177/0890334412452871. | Study design; Publication status
619 | Kimura, LJ, McGee, A, Baird, S, Viloria, J, Nagatsuka, M. Healthy Mothers Healthy Babies: awareness and perceptions of existing breastfeeding and postpartum depression support among parents and perinatal health care providers in Hawai’i. Hawaii J Med Public Health. 2015. 74:101-11. | Intervention/exposure - KQ3; Independent variable - KQ2
620 | Kitsantas, P, Gaffney, KF, Nirmalraj, L, Sari, M. The influence of maternal life stressors on breastfeeding outcomes: a US population-based study. J Matern Fetal Neonatal Med. 2019. 32:1869-1873. doi:10.1080/14767058.2017.1421929. | Mediators/moderators; Intervention/exposure - KQ3
621 | Kivlighan, KT, Murray-Krezan, C, Schwartz, T, Shuster, G, Cox, K. Improved breastfeeding duration with Baby Friendly Hospital Initiative implementation in a diverse and underserved population. Birth. 2020. 47:135-143. doi:10.1111/birt.12468. | Mediators/moderators; Study participants
622 | Kjelland, Kimberly, Corley, Donna, Slusher, Ida, Moe, Krista, Brockopp, Dorothy. The Best for Baby Card: An Evaluation of Factors That Influence Women’s Decisions to Breastfeed. Newborn & Infant Nursing Reviews. 2014. 14:23-27. doi:10.1053/j.nainr.2013.12.007. | Independent variable - KQ2; Study participants
623 | Klimeck Brauner Pissolato, L, Neumaier Alves, C, Alende Prates, L, Antunes Wilhelm, L, Ressel, LB. The Breastfeeding Experience In Recent Mothers View: Contributions For Nursing. Journal of Nursing UFPE / Revista de Enfermagem UFPE. 2015. 9:8771-8777. doi:10.5205/reuol.7696-67533-1-SP-1.0908201502. | Country
624 | Kling, Oms Iii D, Haile, ZT, Francescon, Oms Iii J, Chertok, I. Association Between Method of Delivery and Exclusive Breastfeeding at Hospital Discharge. J Am Osteopath Assoc. 2016. 116:430-9. doi:10.7556/jaoa.2016.087. | Mediators/moderators; Intervention/exposure - KQ3
625 | Knaak, SJ. Contextualising risk, constructing choice: Breastfeeding and good mothering in risk society. Health Risk & Society. 2010. 12:345-355. doi:10.1080/13698571003789666. | Country
626 | Knox-Kazimierczuk, FA, Nommsen-Rivers, L, Ware, J, Graham, C, Conner, N. Exploring the Breastfeeding Experiences of African American Mothers Through a Critical Race Theory Lens. Breastfeeding Medicine. 2021. 16:487-492. doi:10.1089/bfm.2020.0328. | Independent variable - KQ2; Study participants
627 | Ko, JY, Tong, VT, Bombard, JM, Hayes, DK, Davy, J, Perham-Hester, KA. Marijuana use during and after pregnancy and association of prenatal use on birth outcomes: A population-based study. Drug Alcohol Depend. 2018. 187:72-78. doi:10.1016/j.drugalcdep.2018.02.017. | Mediators/moderators; Intervention/exposure - KQ3
628 | Koerber, A, Brice, L, Tombs, E. Breastfeeding and Problematic Integration: Results of a Focus-Group Study. Health Communication. 2012. 27:124-144. doi:10.1080/10410236.2011.571754. | Intervention/exposure - KQ3; Independent variable - KQ2
629 | Koleilat, M, Whaley, SE, Clapp, C. The Impact of COVID-19 on Breastfeeding Rates in a Low-Income Population. Breastfeed Med. 2022. 17:33-37. doi:10.1089/bfm.2021.0238. | Intervention/exposure - KQ3; Independent variable - KQ2
630 | Komninou, S, Fallon, V, Halford, JCG, Harrold, JA. Differences in the emotional and practical experiences of exclusively breastfeeding and combination feeding mothers. Matern Child Nutr. 2017. 13:e12364. doi:10.1111/mcn.12364. | Country
631 | Kopetsky, A, Baker, S, Hobbs, K, Robson, S. Understanding Mothers’ Perceptions of Food Skills: A Qualitative Study. Journal of the Academy of Nutrition and Dietetics. 2021. 121:1339-+. doi:10.1016/j.j.2021.01.001. | Outcome
632 | Kornides, M, Kitsantas, P. Evaluation of breastfeeding promotion, support, and knowledge of benefits on breastfeeding outcomes. Journal of Child Health Care. 2013. 17:264-273. doi:10.1177/1367493512461460. | Mediators/moderators; Study participants
633 | Kortsmit, K, Garfield, C, Smith, RA, Boulet, S, Simon, C, Pazol, K, Kapaya, M, Harrison, L, Barfield, W, Warner, L. Paternal Involvement and Maternal Perinatal Behaviors: Pregnancy Risk Assessment Monitoring System, 2012-2015. Public Health Rep. 2020. 135:253-261. doi:10.1177/0033354920904066. | Intervention/exposure - KQ3; Independent variable - KQ2
634 | Koschmann, KS, Peden-McAlpine, CJ, Chesney, M, Mason, SM, Hooke, MC. Urban, Low-Income, African American Parents’ Experiences and Expectations of Well-Child Care. J Pediatr Nurs. 2021. 60:24-30. doi:10.1016/j.pedn.2021.01.022. | Outcome
635 | Kost, K, Lindberg, L. Pregnancy intentions, maternal behaviors, and infant health: investigating relationships with new measures and propensity score analysis. Demography. 2015. 52:83-111. doi:10.1007/s13524-014-0359-9. | Mediators/moderators; Intervention/exposure - KQ3; Outcome
636 | Kowalski, Mildred, Rudnitzky, Sandra, Williams, Garnet, Aguilar, Magali. New Moms’ Support Groups: English and Hispanic Needs…28th Annual Scientific Session. Nursing Research. 2016. 65:E55-E55. doi:10.1097/NNR.0000000000000152. | Publication status
637 | Kozhimannil, KB, Jou, J, Gjerdingen, DK, McGovern, PM. Access to Workplace Accommodations to Support Breastfeeding after Passage of the Affordable Care Act. Womens Health Issues. 2016. 26:6-13. doi:10.1016/j.whi.2015.08.002. | Mediators/moderators; Study participants
638 | Krans, EE, Cochran, G, Bogen, DL. Caring for Opioid-dependent Pregnant Women: Prenatal and Postpartum Care Considerations. Clin Obstet Gynecol. 2015. 58:370-9. doi:10.1097/grf.0000000000000098. | Study design
639 | Krause, KM, Lovelady, CA, Peterson, BL, Chowdhury, N, Østbye, T. Effect of breast-feeding on weight retention at 3 and 6 months postpartum: data from the North Carolina WIC Programme. Public Health Nutr. 2010. 13:2019-26. doi:10.1017/s1368980010001503. | Outcome
640 | Kronborg, H, Vaeth, M. How are effective breastfeeding technique and pacifier use related to breastfeeding problems and breastfeeding duration?. Birth. 2009. 36:34-42. doi:10.1111/j.1523-536X.2008.00293.x. | Country
641 | Kronborg, Hanne, Væth, Michael. Validation of the Breastfeeding Score—A Simple Screening Tool to Predict Breastfeeding Duration. Nutrients. 2019. 11:2852-2852. doi:10.3390/nu11122852. | Country
642 | Krowchuk, HV. Toward Evidence-Based Practice. Predictors of Breastfeeding Non-Initiation in the N ICU. MCN: The American Journal of Maternal Child Nursing. 2019. 44:366-366. doi:10.1097/NMC.0000000000000577. | Intervention/exposure - KQ3; Study design
643 | Kuhnly, JE. Sustained Breastfeeding and Related Factors for Late Preterm and Early Term Infants. J Perinat Neonatal Nurs. 2018. 32:175-188. doi:10.1097/jpn.0000000000000331. | Mediators/moderators; Study participants
644 | Kuklina, EV. Breastfeeding and cardiometabolic profile in childhood: how infant feeding, preterm birth, socioeconomic status, and obesity may fit into the puzzle. Circulation. 2014. 129:281-284. doi:10.1161/CIRCULATIONAHA.113.006941. | Country; Study design
645 | Kumari, R. Effectiveness of Green Cabbage Leaves (GCL) Vs Hot water bag (HWB) application on Breast Engorgement in Postnatal Mothers. International Journal of Nursing Education. 2019. 11:39-44. doi:10.5958/0974-9357.2019.00061.8. | Country
646 | Kuo, AA, Inkelas, M, Slusser, WM, Maidenberg, M, Halfon, N. Introduction of solid food to young infants. Matern Child Health J. 2011. 15:1185-94. doi:10.1007/s10995-010-0669-5. | Outcome
647 | Laanterä, S, Pietilä, AM, Ekström, A, Pölkki, T. Confidence in breastfeeding among pregnant women. West J Nurs Res. 2012. 34:933-51. doi:10.1177/0193945910396518. | Country
648 | Labbok, MH, Taylor, EC, Nickel, NC. Implementing the ten steps to successful breastfeeding in multiple hospitals serving low-wealth patients in the US: innovative research design and baseline findings. Int Breastfeed J. 2013. 8:5. doi:10.1186/1746-4358-8-5. | Study participants
649 | Ladores, S, Debiasi, L, Currie, E. Breastfeeding Women in Academia: Pursuing Tenure Track Versus “Mommy” Track. Clinical Lactation. 2019. 10:11-16. doi:10.1891/2158-0782.10.1.11. | Outcome
650 | Landau, TV. Breastfeeding case study: New York City--the WIC Program’s vital role in breastfeeding success. Breastfeed Med. 2011. 6:277-9. doi:10.1089/bfm.2011.0067. | Mediators/moderators; Publication status
651 | Lande, MS, Nedberg, IH, Anda, EE. Factors associated with exclusive breastfeeding at hospital discharge: a study using data from the Georgian Birth Registry. International Breastfeeding Journal. 2020. 15:1-10. doi:10.1186/s13006-020-00286-9. | Country
652 | Langdon, KY. Nevada’s Infant at Work Program. Breastfeed Med. 2012. 7:370-1. doi:10.1089/bfm.2012.0077. | Independent variable - KQ2; Outcome; Study participants
653 | Langford, Sarah. Breastfeeding with depression. Essence: Newsletter of the Australian Breastfeeding Association. 2018. 54:16-19. | Intervention/exposure - KQ3; Independent variable - KQ2; Study participants
654 | Lara-Cinisomo, S, McKenney, K, Di Florio, A, Meltzer-Brody, S. Associations Between Postpartum Depression, Breastfeeding, and Oxytocin Levels in Latina Mothers. Breastfeeding Medicine. 2017. 12:436-442. doi:10.1089/bfm.2016.0213. | Mediators/moderators; Intervention/exposure - KQ3
655 | Latina Mothers and the Impact of the Acculturation Process on Breastfeeding: A Qualitative Study. Journal of Nutrition Education & Behavior. 2012. 44:S64-S65. doi:10.1016/j.jneb.2012.03.149. | Publication status
656 | Lau, Y, Htun, TP, Lim, PI, Ho-Lim, S, Klainin-Yobas, P. Maternal, Infant Characteristics, Breastfeeding Techniques, and Initiation: Structural Equation Modeling Approaches. PLoS One. 2015. 10:e0142861. doi:10.1371/journal.pone.0142861. | Country
657 | Lauer, EA, Armenti, K, Henning, M, Sirois, L. Identifying Barriers and Supports to Breastfeeding in the Workplace Experienced by Mothers in the New Hampshire Special Supplemental Nutrition Program for Women, Infants, and Children Utilizing the Total Worker Health Framework. Int J Environ Res Public Health. 2019. 16:529. doi:10.3390/ijerph16040529. | Mediators/moderators; Intervention/exposure - KQ3
658 | Laurent, CP. Whispers2Mom,: A Young Adult Prenatal Text Messaging Intervention. University of Wisconsin-Milwaukee; 2018. | Publication status
659 | Lawrence, RA. Challenges to successful breastfeeding. Breastfeeding Medicine. 2012. 7:1-2. doi:10.1089/bfm.2012.9994. | Study design
660 | Lawrence, RA. Factors that influence breastmilk and a tale from west virginia. Breastfeeding Medicine. 2011. 6:109-110. doi:10.1089/bfm.2011.9991. | Study design
661 | Lebrun-Harris, LA, Sharma, R. Receipt of Prenatal Counseling among Health Center Patients. J Health Care Poor Underserved. 2018. 29:833-842. doi:10.1353/hpu.2018.0063. | Mediators/moderators; Comparator - KQ3
662 | Lee, AI, McCarthy, RJ, Toledo, P, Jones, MJ, White, N, Wong, CA. Epidural Labor Analgesia-Fentanyl Dose and Breastfeeding Success: A Randomized Clinical Trial. Anesthesiology. 2017. 127:614-624. doi:10.1097/ALN.0000000000001793. | Independent variable - KQ2; Study participants
663 | Lee, CHM, O’Leary, J, Kirk, P, Lower, TA. Breastfeeding Outcomes in Washington State: Determining the Effect of Loving Support Peer Counseling Program and Characteristics of Participants at WIC Agencies. J Nutr Educ Behav. 2018. 50:379-387.e1. doi:10.1016/j.jneb.2017.09.002. | Mediators/moderators; Study participants
664 | Lee, HC, Gould, JB, Martin-Anderson, S, Dudley, RA. Breast-milk feeding of very low birth weight infants as a function of hospital demographics. Journal of Perinatology. 2011. 31:S82-S82. doi:10.1038/jp.2010.179. | Publication status
665 | Lee, HC, Gould, JB. Factors influencing breast milk versus formula feeding at discharge for very low birth weight infants in California. J Pediatr. 2009. 155:657-62.e1-2. doi:10.1016/j.jpeds.2009.04.064. | Mediators/moderators; Intervention/exposure - KQ3
666 | Lennon, T, Bakewell, D, Willis, E. The Breastfeeding Employer Supported Time Project: Using a Mentor-Mentee-Based Approach to Establish Workplace Lactation Support in Milwaukee County. J Hum Lact. 2018. 34:47-50. doi:10.1177/0890334417719246. | Outcome
667 | Leonard, SA, Rasmussen, KM. Larger Infant Size at Birth Reduces the Negative Association between Maternal Prepregnancy Body Mass Index and Breastfeeding Duration. Journal of Nutrition. 2011. 141:645-653. doi:10.3945/jn.110.129874. | Intervention/exposure - KQ3; Independent variable - KQ2
668 | Lerner, LB, Baltrushes, RJ, Stolzmann, KL, Garshick, E. Satisfaction of women urologists with maternity leave and childbirth timing. J Urol. 2010. 183:282-6. doi:10.1016/j.juro.2009.08.113. | Study participants
669 | Leruth, C, Goodman, J, Bragg, B, Gray, D. A Multilevel Approach to Breastfeeding Promotion: Using Healthy Start to Deliver Individual Support and Drive Collective Impact. Matern Child Health J. 2017. 21:4-10. doi:10.1007/s10995-017-2371-3. | Mediators/moderators; Comparator - KQ3
670 | Levi, EE, Findley, MK, Avila, K, Bryant, AG. Placement of Levonorgestrel Intrauterine Device at the Time of Cesarean Delivery and the Effect on Breastfeeding Duration. Breastfeed Med. 2018. 13:674-679. doi:10.1089/bfm.2018.0060. | Mediators/moderators; Study participants
671 | Lewis, JA. Costs Related to Promoting Breastfeeding Among Urban Low- Income Women. MCN: The American Journal of Maternal Child Nursing. 2012. 37:277-277. | Outcome
672 | Lewkowitz, AK, Raghuraman, N, López, JD, Macones, GA, Cahill, AG. Infant Feeding Practices and Perceived Optimal Breastfeeding Interventions among Low-Income Women Delivering at a Baby-Friendly Hospital. Am J Perinatol. 2019. 36:669-677. doi:10.1055/s-0038-1676485. | Mediators/moderators; Intervention/exposure - KQ3
673 | Li, CM, Li, R, Ashley, CG, Smiley, JM, Cohen, JH, Dee, DL. Associations of Hospital Staff Training and Policies with Early Breastfeeding Practices. Journal of Human Lactation. 2014. 30:88-96. doi:10.1177/0890334413484551. | Independent variable - KQ2; Study participants
674 | Li, JY, Huang, Y, Huang, YY, Shen, Q, Zhou, WB, Redding, SR, Ouyang, YQ. Experience predicts the duration of exclusive breastfeeding: The serial mediating roles of attitude and self-efficacy. Birth. 2021. 48:397-405. doi:10.1111/birt.12549. | Country
675 | Linares, AM, Rayens, MK, Dozier, A, Wiggins, A, Dignan, MB. Factors influencing exclusive breastfeeding at 4 months postpartum in a sample of urban Hispanic mothers in Kentucky. J Hum Lact. 2015. 31:307-14. doi:10.1177/0890334414565711. | Intervention/exposure - KQ3; Independent variable - KQ2
676 | Linares, AM, Wambach, K, Rayens, MK, Wiggins, A, Coleman, E, Dignan, MB. Modeling the Influence of Early Skin-to-Skin Contact on Exclusive Breastfeeding in a Sample of Hispanic Immigrant Women. J Immigr Minor Health. 2017. 19:1027-1034. doi:10.1007/s10903-016-0380-8. | Mediators/moderators; Comparator
677 | Linares, AM, Bailey, DF, Ashford, K. Enabling Nurse Students to Achieve Their Breastfeeding Goals. Clinical Lactation. 2020. 11:65-73. doi:10.1891/CLINLACT-D-18-00021. | Intervention/exposure - KQ3; Comparator
678 | Lind, JN, Perrine, CG, Li, R, Scanlon, KS, Grummer-Strawn, LM. Racial disparities in access to maternity care practices that support breastfeeding - United States, 2011. MMWR Morb Mortal Wkly Rep. 2014. 63:725-8. | Outcome
679 | Lindberg, L, Maddow-Zimet, I, Kost, K, Lincoln, A. Pregnancy intentions and maternal and child health: an analysis of longitudinal data in Oklahoma. Matern Child Health J. 2015. 19:1087-96. doi:10.1007/s10995-014-1609-6. | Mediators/moderators; Intervention/exposure - KQ3
680 | Lindberg, Nina, Berglund, Anna-Lena. Mothers’ experiences of feeding babies born with cleft lip and palate. Scandinavian Journal of Caring Sciences. 2014. 28:66-73. doi:10.1111/scs.12048. | Country
681 | Lindberg, SM, Adams, AK, Prince, RJ. Early predictors of obesity and cardiovascular risk among American Indian children. Matern Child Health J. 2012. 16:1879-86. doi:10.1007/s10995-012-1024-9. | Outcome
682 | Linden, K, Berg, M, Sparud-Lundin, C. Web-based information for pregnant women and new mothers with type 1 diabetes- a description of the development process. Bmc Medical Informatics and Decision Making. 2012. 12:9. doi:10.1186/1472-6947-12-134. | Country
683 | Linden, K, Berg, M, Adolfsson, A, Sparud-Lundin, C. Well-being, diabetes management and breastfeeding in mothers with type 1 diabetes – An explorative analysis. Sexual & Reproductive HealthCare. 2018. 15:77-82. doi:10.1016/j.srhc.2017.12.004. | Country
684 | Lippitt, M, Reese Masterson, A, Sierra, A, Davis, AB, White, MA. An Exploration of Social Desirability Bias in Measurement of Attitudes toward Breastfeeding in Public. Journal of Human Lactation. 2014. 30:358-366. doi:10.1177/0890334414529020. | Outcome
685 | Lis-Kuberka, J, Orczyk-Pawiłowicz, M. Polish Women Have Moderate Knowledge of Gestational Diabetes Mellitus and Breastfeeding Benefits. Int J Environ Res Public Health. 2021. 18:10409. doi:10.3390/ijerph181910409. | Country
686 | Little, EE, Legare, CH, Carver, LJ. Mother-Infant Physical Contact Predicts Responsive Feeding among U.S. Breastfeeding Mothers. Nutrients. 2018. 10:1251. doi:10.3390/nu10091251. | Independent variable - KQ2; Study participants
687 | Little, SH, Motohara, S, Plegue, M, Medaugh, C, Sen, A, Ruffin, MT. Japanese Women’s Concerns and Satisfaction With Pregnancy Care in the United States. J Perinat Educ. 2020. 29:152-160. doi:10.1891/j-pe-d-19-00009. | Mediators/moderators; Intervention/exposure - KQ3
688 | Liu, J, Pang, EM, Iacob, A, Simonian, A, Phibbs, CS, Profit, J. Evaluating Care in Safety Net Hospitals: Clinical Outcomes and Neonatal Intensive Care Unit Quality of Care in California. J Pediatr. 2022. 243:99-106.e3. doi:10.1016/j.jpeds.2021.12.003. | Mediators/moderators; Intervention/exposure - KQ3
689 | Liu, J, Parker, MG, Lu, T, Conroy, SM, Oehlert, J, Lee, HC, Gomez, SL, Shariff-Marco, S, Profit, J. Racial and Ethnic Disparities in Human Milk Intake at Neonatal Intensive Care Unit Discharge among Very Low Birth Weight Infants in California. J Pediatr. 2020. 218:49-56.e3. doi:10.1016/j.jpeds.2019.11.020. | Mediators/moderators; Outcome
690 | Liu, L, Zhu, J, Yang, J, Wu, M, Ye, B. The Effect of a Perinatal Breastfeeding Support Program on Breastfeeding Outcomes in Primiparous Mothers. Western Journal of Nursing Research. 2017. 39:906-923. doi:10.1177/0193945916670645. | Country
691 | Llewellyn, R, Berger, S, Carty, S, Randall, P, Jahnke, K, Thompson, L. Breastfeeding friendly pharmacies: a setting with potential. Australian and New Zealand Journal of Public Health. 2017. 41:322-323. doi:10.1111/1753-6405.12633. | Outcome
692 | Loewenberg Weisband, Y, Keim, SA, Keder, LM, Geraghty, SR, Gallo, MF. Early Breast Milk Pumping Intentions Among Postpartum Women. Breastfeed Med. 2017. 12:28-32. doi:10.1089/bfm.2016.0142. | Mediators/moderators; Intervention/exposure - KQ3
693 | Lööf-Johanson, M, Foldevi, M, Rudebeck, CE. Breastfeeding as a Specific Value in Women’s Lives: The Experiences and Decisions of Breastfeeding Women. Breastfeeding Medicine. 2013. 8:38-44. doi:10.1089/bfm.2012.0008. | Country
694 | Lopes, GC, Gonçalves, AC, Gouveia, HG, Armellini, CJ. Attention to childbirth and delivery in a university hospital: comparison of practices developed after Network Stork. Rev Lat Am Enfermagem. 2019. 27:e3139. doi:10.1590/1518-8345.2643-3139. | Country
695 | Lori, JR, Chuey, M, Munro-Kramer, ML, Ofosu-Darkwah, H, Adanu, RMK. Increasing postpartum family planning uptake through group antenatal care: a longitudinal prospective cohort design. Reproductive Health. 2018. 15:N.PAG-N.PAG. doi:10.1186/s12978-018-0644-y. | Country
696 | Louis-Jacques, AF, Marhefka, SL, Brumley, J, Schafer, EJ, Taylor, TI, Brown, AJ, Livingston, TA, Spatz, DL, Miller, EM. Historical Antecedents of Breastfeeding for African American Women: from the Pre-Colonial Period to the Mid-Twentieth Century. Journal of Racial and Ethnic Health Disparities. 2020. 7:1003-1012. doi:10.1007/s40615-020-00727-5. | Study design
697 | Louis-Jacques, AF, Schafer, EJ, Livingston, TA, Logan, RG, Marhefka, SL. Modesty and Security: Attributes Associated with Comfort and Willingness to Engage in Telelactation. Children (Basel). 2021. 8:271. doi:10.3390/children8040271. | Outcome
698 | Louis-Jacques, AF, Vereen, S, Hernandez, I, Običan, SG, Deubel, TF, Miller, EM, Spatz, DL, Wilson, RE. Impact of Doula-Led Lactation Education on Breastfeeding Outcomes in Low-Income, Minoritized Mothers. J Perinat Educ. 2021. 30:203-212. doi:10.1891/j-pe-d-20-00022. | Mediators/moderators; Comparator - KQ3
699 | Louis-Jacques, AF, Wilson, R, Dean, K, Hernandez, I, Spatz, D, Običan, S. Improving Drug Exposure Knowledge During Lactation: Quality Improvement Initiative in Low-Income Women. Breastfeed Med. 2020. 15:140-146. doi:10.1089/bfm.2019.0222. | Mediators/moderators; Intervention/exposure - KQ3
700 | LoVerde, B, Falck, A, Donohue, P, Hussey-Gardener, B. Supports and Barriers to the Provision of Human Milk by Mothers of African American Preterm Infants. Adv Neonatal Care. 2018. 18:179-188. doi:10.1097/anc.0000000000000477. | Intervention/exposure - KQ3; Study participants
701 | Lucas, A, McMahon, PM, Asling, MB, Knobloch, A, Kosh, E, Sims, K. Assessing child care providers’ knowledge and attitudes regarding support of breastfeeding in a region with low breastfeeding prevalence. J Hum Lact. 2013. 29:556-63. doi:10.1177/0890334413497259. | Outcome; Study participants
702 | Lucas, R, Judge, M, Sajdlowska, J, Cong, X, McGrath, JM, Brandon, D. Effect of Maternal Body Mass Index on Infant Breastfeeding Behaviors and Exclusive Direct Breastfeeding. J Obstet Gynecol Neonatal Nurs. 2015. 44:772-83. doi:10.1111/1552-6909.12755. | Mediators/moderators; Intervention/exposure - KQ3; Independent variable - KQ2
703 | Lucas, R, Zhang, Y, Walsh, SJ, Evans, H, Young, E, Starkweather, A. Efficacy of a Breastfeeding Pain Self-Management Intervention: A Pilot Randomized Controlled Trial. Nursing Research. 2019. 68:E1-E10. doi:10.1097/NNR.0000000000000336. | Outcome
704 | Luecken, LJ, Jewell, SL, MacKinnon, DP. Maternal acculturation and the growth of impoverished Mexican American infants. Obesity (Silver Spring). 2017. 25:445-451. doi:10.1002/oby.21743. | Intervention/exposure - KQ3; Outcome
705 | Lundeen, S, Sorensen, S, Bland, M, George, S, Snyder, B. Nurses’ Perspectives on the Process of Attaining Baby-Friendly Designation. Nurs Womens Health. 2016. 20:277-87. doi:10.1016/j.nwh.2016.03.004. | Study participants
706 | Lundquist, A, McBride, BA, Donovan, SM, Kieffer, A. An Exploratory Look at the Role of Childcare Providers as a Support and Resource for Breastfeeding Mothers. Breastfeed Med. 2019. 14:313-319. doi:10.1089/bfm.2018.0091. | Publication status
707 | Lussier, MM, Tosi, L, Brownell, EA. Predictors of Mother’s Own Milk Feeding at Discharge in Preterm Infants. Adv Neonatal Care. 2019. 19:468-473. doi:10.1097/anc.0000000000000678. | Mediators/moderators; Intervention/exposure - KQ3
708 | Ly, K. Changing norms: addressing breastfeeding inequalities. Community Practitioner. 2009. 82:12-13. | Country
709 | Lytton, TD, Dennison, BA, Nguyen, TQ, Jurkowski, JM. There Is More to Transparency than Meets the Eye: The Impact of Mandatory Disclosure Laws Aimed at Promoting Breastfeeding. Am J Law Med. 2014. 40:393-415. | Outcome
710 | Faghani Aghoozi, M, Karimi Khoshal, M, Fayazi, M, Tork Zahrani, S, Amerian, M. On the Relationship between Social Support and Early breastfeeding Termination. Nursing & Midwifery Care Journal. 2020. 9:1-11. | Country
711 | Ma, X, Liu, J, Smith, M. WIC participation and breastfeeding in South Carolina: updates from PRAMS 2009-2010. Matern Child Health J. 2014. 18:1271-9. doi:10.1007/s10995-013-1362-2. | Mediators/moderators; Study participants
712 | MacArthur, C, Jolly, K, Ingram, L, Freemantle, N, Dennis, CL, Hamburger, R, Brown, J, Chambers, J, Khan, K. Antenatal peer support workers and initiation of breast feeding: cluster randomised controlled trial. Bmj. 2009. 338:b131. doi:10.1136/bmj.b131. | Country
713 | MacMillan Uribe, AL, Olson, BH. Exploring Healthy Eating and Exercise Behaviors Among Low-Income Breastfeeding Mothers. J Hum Lact. 2019. 35:59-70. doi:10.1177/0890334418768792. | Intervention/exposure - KQ3; Independent variable - KQ2
714 | MacNamara, MM, Moren, K, Taylor, LE, Taylor, JS. State-wide support for physician-mothers who are breastfeeding. Med Health R I. 2012. 95:9-13. | Study design
715 | Madrid Muñoz, R, Cano, CC, Cortés Rojas, R. The impact of the extension of the post-natal in the adherence to breastfeeding Cohort study. Rev Chil Pediatr. 2018. 89:484-490. doi:10.4067/s0370-41062018005000701. | Country
716 | Magner, A, Phillipi, CA. Using a wellness program to promote a culture of breastfeeding in the workplace: Oregon Health & Science University’s experience. J Hum Lact. 2015. 31:40-2. doi:10.1177/0890334414554262. | Outcome
717 | Magri, EP, Hylton-McGuire, K. Transforming a care delivery model to increase breastfeeding. MCN Am J Matern Child Nurs. 2013. 38:177-82; quiz 183-4. doi:10.1097/NMC.0b013e3182836af7. | Study participants
718 | Mahdavi, R, Nikniaz, L, Pourghassem, Gargari, Ghaemmaghami, J. Evaluation of zinc, copper and iron concentrations in breast milk of mothers belonging to different economic classes and their corelations with infants growth. Journal of Shaheed Sadoughi University of Medical Sciences & Health Services. 2011. 19:11p-11p. | Language
719 | Maher, MD. Perinatal Risks and Outcomes of Latina Migrant Farmworker Women. University of Rochester; 2012. | Publication status
720 | Majee, W, Jefferson, UT, Goodman, LR, Olsberg, JE. Four Years Later: Rural Mothers’ and Employers’ Perspectives on Breastfeeding Barriers Following the Passage of the Affordable Care Act. J Health Care Poor Underserved. 2016. 27:1110-25. doi:10.1353/hpu.2016.0111. | Study participants
721 | Making breastfeeding fashionable’: the story of Little Angels. Practising Midwife. 2009. 12:26-27. | Country
722 | Makk, S. More breastfeeding support needed. World of Irish Nursing & Midwifery. 2015. 23:50-50. | Country
723 | Mandal, B, Roe, BE, Fein, SB. The differential effects of full-time and part-time work status on breastfeeding. Health Policy. 2010. 97:79-86. doi:10.1016/j.healthpol.2010.03.006. | Study participants
724 | Mandal, B, Roe, BE, Fein, SB. Work and breastfeeding decisions are jointly determined for higher socioeconomic status US mothers. Review of Economics of the Household. 2014. 12:237-257. doi:10.1007/s11150-012-9152-y. | Mediators/moderators; Intervention/exposure - KQ3; Study participants
725 | Manganaro, R, Marseglia, L, Mamì, C, Paolata, A, Gargano, R, Mondello, M, Puliafito, A, Gemelli, M. Effects of hospital policies and practices on initiation and duration of breastfeeding. Child Care Health Dev. 2009. 35:106-11. doi:10.1111/j.1365-2214.2008.00899.x. | Country
726 | Mao, CY, Narang, S, Lopreiato, J. Breastfeeding practices in military families: a 12-month prospective population-based study in the national capital region. Mil Med. 2012. 177:229-34. doi:10.7205/milmed-d-11-00181. | Mediators/moderators; Intervention/exposure - KQ3
727 | Maralani, V, Stabler, S. Intensive Parenting: Fertility and Breastfeeding Duration in the United States. Demography. 2018. 55:1681-1704. doi:10.1007/s13524-018-0710-7. | Mediators/moderators; Intervention/exposure - KQ3
728 | Margarit, MB, Rojas, RG, del Castillo, MÁ. Personalising birth, with empowerment and transversal vision. International Journal of Integrated Care (IJIC). 2016. 16:1-2. doi:10.5334/ijic.2971. | Country; Publication status
729 | Marhefka, SL, Sharma, V, Schafer, EJ, Turner, D, Falope, O, Louis-Jacques, A, Wachira, MM, Livingston, T, Roig-Romero, RM. ‘Why do we need a policy?’ Administrators’ perceptions on breast-feeding-friendly childcare. Public Health Nutr. 2019. 22:553-563. doi:10.1017/s1368980018002914. | Outcome
730 | Marinho da Silva, A, Salustino dos Santos, MC, de Melo Silva, SR, Ferreira, FÂ, de Souza Cabral Freitas, R, Alcoforado dos Santos, RE, Tomé Gouveia, M. Exclusive Breastfeeding: Obstacles Presented By Primiparous Women. Journal of Nursing UFPE / Revista de Enfermagem UFPE. 2018. 12:3205-3211. doi:10.5205/1981-8963-v12i12a236599p3205-3211-2018. | Country
731 | Marlow, Fiona. Breastfeeding, stigma and non-judgemental care. Australian Midwifery News. 2016. 16:25-26. | Study design
732 | Marshall, NE, Lau, B, Purnell, JQ, Thornburg, KL. Impact of maternal obesity and breastfeeding intention on lactation intensity and duration. Maternal & Child Nutrition. 2019. 15:N.PAG-N.PAG. doi:10.1111/mcn.12732. | Mediators/moderators; Intervention/exposure - KQ3
733 | Martin, H, van Wijngaarden, E, Seplaki, CL, Stringer, J, Williams, GC, Dozier, AM. Breastfeeding Motivation Predicts Infant Feeding Intention and Outcomes: Evaluation of a Novel Adaptation of the Treatment Self-Regulation Questionnaire. Journal of Human Lactation. 2022. 38:236-247. doi:10.1177/08903344211032128. | Mediators/moderators; Study participants
734 | Martin, SE, Drake, E, Yoder, L, Gibson, M, Litke, CA. Active Duty Women’s Perceptions of Breast-Feeding Support in the Military Setting. Mil Med. 2015. 180:1154-60. doi:10.7205/milmed-d-14-00498. | Study participants
735 | Martin, V, Greatrex-White, S. An evaluation of factors influencing feeding in babies with a cleft palate with and without a cleft lip. Journal of Child Health Care. 2014. 18:72-83. doi:10.1177/1367493512473853. | Country
736 | Martinez, JL, Chapman, DJ, Pérez-Escamilla, R. Prepregnancy Obesity Class Is a Risk Factor for Failure to Exclusively Breastfeed at Hospital Discharge among Latinas. J Hum Lact. 2016. 32:258-68. doi:10.1177/0890334415622638. | Mediators/moderators; Intervention/exposure - KQ3
737 | Martinez-Brockman, JL, Harari, N, Goeschel, L, Bozzi, V, Pérez-Escamilla, R. A qualitative analysis of text message conversations in a breastfeeding peer counselling intervention. Matern Child Nutr. 2020. 16:e12904. doi:10.1111/mcn.12904. | Outcome; Data type
738 | Martinez-Brockman, JL, Shebl, FM, Harari, N, Pérez-Escamilla, R. An assessment of the social cognitive predictors of exclusive breastfeeding behavior using the Health Action Process Approach. Soc Sci Med. 2017. 182:106-116. doi:10.1016/j.socscimed.2017.04.014. | Intervention/exposure - KQ3; Independent variable - KQ2
739 | Martins GuimarÃ£es, L, Rangel da Silva, L, Feliciano Maques, L. Management Of Breastfeeding For Mothers, Nursing Professionals, Which Work In A Maternity. Journal of Nursing UFPE / Revista de Enfermagem UFPE. 2012. 6:2030-2036. | Country
740 | Masho, SW, Morris, MR, Wallenborn, JT. Role of Marital Status in the Association between Prepregnancy Body Mass Index and Breastfeeding Duration. Womens Health Issues. 2016. 26:468-75. doi:10.1016/j.whi.2016.05.004. | Mediators/moderators; Intervention/exposure - KQ3
741 | Mathews, ME, Leerkes, EM, Lovelady, CA, Labban, JD. Psychosocial predictors of primiparous breastfeeding initiation and duration. J Hum Lact. 2014. 30:480-7. doi:10.1177/0890334414537707. | Mediators/moderators; Intervention/exposure - KQ3
742 | Matias, SL, Dewey, KG, Quesenberry, CP, Jr, Gunderson, EP. Maternal prepregnancy obesity and insulin treatment during pregnancy are independently associated with delayed lactogenesis in women with recent gestational diabetes mellitus. Am J Clin Nutr. 2014. 99:115-21. doi:10.3945/ajcn.113.073049. | Outcome
743 | Matos, NJ, Sousa de Oliveira, N, Figueiredo Coelho, MM, Melo Dodt, RC, Moreira Moura, DJ. Perception And Support Given By Father In Maintenance Of Breastfeeding. Journal of Nursing UFPE / Revista de Enfermagem UFPE. 2015. 9:7819-7825. doi:10.5205/reuol.6121-57155-1-ED.0905201511. | Country
744 | Mattiello, R, Kotoski, A, Ayala, CO, Recha, CL, Quiroga, CV, Machado, CR, Roxo, CD, Varela, FH, Couto, GT, Cassao, G, Lopes, JB, Goncalves, JIB, da Silva, JF, de Barh, MB, Rocha, ND, de Albuquerque, NS, Dalla Corte, RA, Bernardes, R, Richter, SA, Rossi, T, Santos, IS. Prevalence and factors associated with no intention to exclusively breastfeed for the first 6 months of life. Jornal De Pediatria. 2022. 98:39-45. doi:10.1016/j.jped.2021.02.006. | Country
745 | Mc Loughlin, G. Rooming-in for new mother and infant versus separate care for increasing the duration of breastfeeding. International Journal of Nursing Practice (John Wiley & Sons, Inc.). 2018. 24:1-2. doi:10.1111/ijn.12633. | Study design
746 | McAuliffe, CG, Rialon, KL, Hipp, DM, Krucoff, KB. Multispecialty Resident Perspectives on Parental Leave Policies. J Grad Med Educ. 2019. 11:362-364. doi:10.4300/jgme-d-19-00231.1. | Mediators/moderators; Study participants
747 | McBride, M, Haile, ZT. Association Between Electronic Nicotine Delivery Systems Use and Breastfeeding Duration. Breastfeed Med. 2021. 16:886-893. doi:10.1089/bfm.2021.0132. | Mediators/moderators; Intervention/exposure - KQ3; Study participants
748 | McCardel, RE, Padilla, HM. Assessing Workplace Breastfeeding Support Among Working Mothers in the United States. Workplace Health Saf. 2020. 68:182-189. doi:10.1177/2165079919890358. | Study participants
749 | McCarter-Spaulding, D, Gore, R. Breastfeeding self-efficacy in women of African descent. J Obstet Gynecol Neonatal Nurs. 2009. 38:230-43. doi:10.1111/j.1552-6909.2009.01011.x. | Mediators/moderators; Intervention/exposure - KQ3
750 | McCarter-Spaulding, D, Lucas, J, Gore, R. Employment and breastfeeding outcomes in a sample of black women in the United States. J Natl Black Nurses Assoc. 2011. 22:38-45. | Intervention/exposure - KQ3; Comparator - KQ2
751 | McCoy, MB, Geppert, J, Dech, L, Richardson, M. Associations Between Peer Counseling and Breastfeeding Initiation and Duration: An Analysis of Minnesota Participants in the Special Supplemental Nutrition Program for Women, Infants, and Children (WIC). Matern Child Health J. 2018. 22:71-81. doi:10.1007/s10995-017-2356-2. | Mediators/moderators; Study participants
752 | McCoy, MB, Heggie, P. In-Hospital Formula Feeding and Breastfeeding Duration. Pediatrics. 2020. 146:e20192946. doi:10.1542/peds.2019-2946. | Mediators/moderators; Intervention/exposure - KQ3
753 | McFadden, A, Erikson, SL. How Nurses Come to Race: Racialization in Public Health Breastfeeding Promotion. ANS Adv Nurs Sci. 2020. 43:E11-e24. doi:10.1097/ans.0000000000000288. | Study participants
754 | McGinnis, S, Lee, E, Kirkland, K, Miranda-Julian, C, Greene, R. Let’s Talk About Breastfeeding: The Importance of Delivering a Message in a Home Visiting Program. Am J Health Promot. 2018. 32:989-996. doi:10.1177/0890117117723802. | Mediators/moderators; Study participants
755 | McGuire, E, Curtis, C, Duffy, RM. Fertile ground: reproductive health consideration in mental health ward policy. Ir J Psychol Med. 2020. 1-6. doi:10.1017/ipm.2020.27. | Country; Outcome
756 | McInnes, RJ, Shepherd, AJ, Cheyne, H, Niven, C. Infant feeding in the neonatal unit. Matern Child Nutr. 2010. 6:306-17. doi:10.1111/j.1740-8709.2009.00210.x. | Country
757 | McKean, M, Caughey, AB, Leong, RE, Wong, A, Cabana, MD. The Timing of Infant Food Introduction in Families With a History of Atopy. Clin Pediatr (Phila). 2015. 54:745-51. doi:10.1177/0009922815584927. | Outcome
758 | McKechnie, AC, Tluczek, A, Henriques, JB. Maternal Variables Influencing Duration of Breastfeeding Among Low-Income Mothers. Infant Child Adolesc Nutr. 2009. 1:126-132. doi:10.1177/1941406409334379. | Mediators/moderators; Intervention/exposure - KQ3
759 | McKenzie, SA, Rasmussen, KM, Garner, CD. Experiences and Perspectives About Breastfeeding in “Public”: A Qualitative Exploration Among Normal-Weight and Obese Mothers. J Hum Lact. 2018. 34:760-767. doi:10.1177/0890334417751881. | Study participants
760 | McKittrick, MM, Khaki, S, Gievers, L, Larson, IA. Clinical and Sociodemographic Factors Associated With Human Donor Milk Supplementation in Term Newborns. Hosp Pediatr. 2020. 10:489-495. doi:10.1542/hpeds.2019-0259. | Outcome
761 | McRae, MJ. Exclusive Breastfeeding, 24-Hour Rooming-In, and the Importance of Women’s Informed Choices. Nursing for Women’s Health. 2019. 23:309-315. doi:10.1016/j.nwh.2019.05.003. | Intervention/exposure - KQ3; Independent variable - KQ2
762 | McShane, M, Moffatt, FW, MacDonald, M, Carson, G, White, M. The Meaning of the Breastfeeding Experience for Mothers in Critical Care…Dynamics of Critical Care 2016 in Charlottetown, PE, September 25-27, 2016. Canadian Journal of Critical Care Nursing. 2016. 27:28-29. | Publication status
763 | Mehta, UJ, Siega-Riz, AM, Herring, AH, Adair, LS, Bentley, ME. Maternal obesity, psychological factors, and breastfeeding initiation. Breastfeed Med. 2011. 6:369-76. doi:10.1089/bfm.2010.0052. | Mediators/moderators; Intervention/exposure - KQ3
764 | Mercer, AM, Teasley, SL, Hopkinson, J, McPherson, DM, Simon, SD, Hall, RT. Evaluation of a breastfeeding assessment score in a diverse population. J Hum Lact. 2010. 26:42-8. doi:10.1177/0890334409344077. | Mediators/moderators; Intervention/exposure - KQ3
765 | Merewood, A, Burnham, L, Berger, J, Gambari, A, Safon, C, Beliveau, P, Logan-Hurt, T, Nickel, N. Assessing the impact of a statewide effort to improve breastfeeding rates: A RE-AIM evaluation of CHAMPS in Mississippi. Matern Child Nutr. 2022. 18:e13370. doi:10.1111/mcn.13370. | Study design; Study participants; Other (Same data presented in another paper)
766 | Merjonen, P, Jokela, M, Pulkki-Råback, L, Hintsanen, M, Raitakari, OT, Viikari, J, Keltikangas-Järvinen, L. Breastfeeding and offspring hostility in adulthood. Psychotherapy & Psychosomatics. 2011. 80:371-373. | Country
767 | Messiah, SE, Atem, F, Lebron, C, Ofori, A, Mathew, MS, Chang, C, Natale, RA. Comparison of Early Life Obesity-Related Risk and Protective Factors in Non-Hispanic Black Subgroups. Matern Child Health J. 2020. 24:1130-1137. doi:10.1007/s10995-020-02979-3. | Mediators/moderators; Outcome
768 | Messito, MJ, Gross, M, Mendelsohn, A, Gross, R. Belief That Exclusive Breast Milk Is Best: Breastfeeding Knowledge and Country of Origin in Low-Income Latina Pregnant Women. Journal of Nutrition Education & Behavior. 2013. 45:S60-S60. doi:10.1016/j.jneb.2013.04.159. | Publication status
769 | Messito, MJ, Katzow, MW, Mendelsohn, AL, Gross, RS. Starting Early Program Impacts on Feeding at Infant 10 Months Age: A Randomized Controlled Trial. Child Obes. 2020. 16:S4-s13. doi:10.1089/chi.2019.0236. | Outcome
770 | Metallinos-Katsaras, E, Brown, L, Colchamiro, R. Maternal WIC participation improves breastfeeding rates: a statewide analysis of WIC participants. Matern Child Health J. 2015. 19:136-43. doi:10.1007/s10995-014-1504-1. | Mediators/moderators; Intervention/exposure - KQ3
771 | Metz, TD, Borgelt, LM. Marijuana Use in Pregnancy and While Breastfeeding. Obstetrics and Gynecology. 2018. 132:1198-1210. doi:10.1097/aog.0000000000002878. | Study design
772 | Mi, B, Liu, H, Wang, Y, Small, H, Surguy-Bowers, A, Rideout, TC, Cameron, CE, Lehman, HK, Starke, K, Wen, X. Infant age at egg introduction and malnutrition-related child growth in the United States. Matern Child Nutr. 2022. 18:e13390. doi:10.1111/mcn.13390. | Outcome
773 | Mickens, AD, Modeste, N, Montgomery, S, Taylor, M. Peer support and breastfeeding intentions among black WIC participants. J Hum Lact. 2009. 25:157-62. doi:10.1177/0890334409332438. | Outcome
774 | Middlemiss, W, Glaman, R, Seddio, K, Suerken, CK, Reboussin, BA, Daniel, SS, Payne, CC, Leerkes, E, Grzywacz, JG. Supporting lower-income working women to initiate breastfeeding: Learning who is breastfeeding and what helps. J Am Assoc Nurse Pract. 2018. 30:519-528. doi:10.1097/jxx.0000000000000077. | Mediators/moderators; Intervention/exposure - KQ3
775 | Midgley, EJ. Improving breast feeding rates: experience of a new mum. BMJ: British Medical Journal (Overseas & Retired Doctors Edition). 2009. 338:557-557. | Country
776 | Mieso, BR, Burrow, H, Lam, SK. Beyond Statistics: Uncovering the Roots of Racial Disparities in Breastfeeding. Pediatrics. 2021. 147: e2020037887. doi:10.1542/peds.2020-037887. | Study design
777 | Mijal, RS, Holzman, CB. Blood cadmium levels in women of childbearing age vary by race/ethnicity. Environ Res. 2010. 110:505-12. doi:10.1016/j.envres.2010.02.007. | Outcome
778 | Miller, EM, Louis-Jacques, AF, Deubel, TF, Hernandez, I. One Step for a Hospital, Ten Steps for Women: African American Women’s Experiences in a Newly Accredited Baby-Friendly Hospital. J Hum Lact. 2018. 34:184-191. doi:10.1177/0890334417731077. | Mediators/moderators; Intervention/exposure - KQ3
779 | Miller-Graff, LE, Ahmed, AH, Paulson, JL. Intimate Partner Violence and Breastfeeding Outcomes in a Sample of Low-Income Women. J Hum Lact. 2018. 34:494-502. doi:10.1177/0890334418776217. | Study participants
780 | Miranda e Silva, C, Pereira, SCL, Passos, IR, dos Santos, LC. Factors associated with skin to skin contact between mother/son and breastfeeding in the delivery room. Revista De Nutricao-Brazilian Journal of Nutrition. 2016. 29:457-471. doi:10.1590/1678-98652016000400002. | Country; Language
781 | Mirkovic, KR, Perrine, CG, Scanlon, KS, Grummer-Strawn, LM. Maternity leave duration and full-time/part-time work status are associated with US mothers’ ability to meet breastfeeding intentions. J Hum Lact. 2014. 30:416-9. doi:10.1177/0890334414543522. | Mediators/moderators; Study participants
782 | Mirkovic, KR, Perrine, CG, Scanlon, KS. Paid Maternity Leave and Breastfeeding Outcomes. Birth. 2016. 43:233-9. doi:10.1111/birt.12230. | Mediators/moderators; Study participants
783 | Mitchell-Box, K, Braun, KL. Fathers’ thoughts on breastfeeding and implications for a theory-based intervention. J Obstet Gynecol Neonatal Nurs. 2012. 41:E41-50. doi:10.1111/j.1552-6909.2012.01399.x. | Study participants
784 | Mizrak Sahin, B, Ozerdogan, N, Ozdamar, K, Gursoy, E. Factors affecting breastfeeding motivation in primiparious mothers: An application of breastfeeding motivation scale based on self-determination theory. Health Care Women Int. 2019. 40:637-652. doi:10.1080/07399332.2018.1526289. | Country
785 | Mohd Shukri, NH, Wells, J, Fewtrell, M. Differences in maternal characteristics and their associations with breastfeeding attitudes among primiparous mothers. Midwifery. 2021. 95:N.PAG-N.PAG. doi:10.1016/j.midw.2021.102931. | Country
786 | Moimaz, SAS, Ros, DD, Saliba, TA, Saliba, NA. A quantitative and qualitative study of exclusive breastfeeding intention by high-risk pregnant women. Ciencia & Saude Coletiva. 2020. 25:3657-3668. doi:10.1590/1413-81232020259.30002018. | Country; Language
787 | Mojab, CG. Pandora’s box is already open: answering the ongoing call to dismantle institutional oppression in the field of breastfeeding. J Hum Lact. 2015. 31:32-5. doi:10.1177/0890334414554261. | Study design
788 | Moleti, CA. CenteringPregnancy(TM) Implementation and its Effect on Preterm Birth and Low Birthweight. Walden University; 2015. | Publication status
789 | Mollard, E, Wittmaack, A. Experiences of Women Who Gave Birth in US Hospitals During the COVID-19 Pandemic. J Patient Exp. 2021. 8:2374373520981492. doi:10.1177/2374373520981492. | Outcome
790 | Money For Breastfeeding. Midwives. 2013. 16:9-9. | Country; Study design
791 | Monica, KC, du Plessis, RA. Discussion of the health benefits of breastfeeding within small groups. Community Pract. 2011. 84:31-4. | Outcome
792 | Monteiro Gomes, AL, Balaminut, T, Braña Lopez, S, de Araújo do Espírito Santo Pontes, K, Silvan Scochi, CGr, Moreira Christoffel, M. Breastfeeding of premature infants at a child-friendly hospital: from hospital discharge to home. Rev Rene. 2017. 18:810-817. doi:10.15253/2175-6783.2017000600015. | Country
793 | Montgomery Rice, V. Giving “All” Babies a Great Start, Nutrition Matters. Breastfeed Med. 2018. 13:520-523. doi:10.1089/bfm.2018.0130. | Study design
794 | Monvillers, S, Tchaconas, A, Li, R, Adesman, A, Keim, SA. Characteristics of and Sources of Support for Women Who Breastfed Multiples for More than 12 Months. Breastfeed Med. 2020. 15:213-223. doi:10.1089/bfm.2019.0237. | Mediators/moderators; Intervention/exposure - KQ3
795 | Moon, RY, Hauck, FR, Colson, ER, Kellams, AL, Geller, NL, Heeren, T, Kerr, SM, Drake, EE, Tanabe, K, McClain, M, Corwin, MJ. The Effect of Nursing Quality Improvement and Mobile Health Interventions on Infant Sleep Practices: A Randomized Clinical Trial. Jama. 2017. 318:351-359. doi:10.1001/jama.2017.8982. | Outcome
796 | Moon, RY, LoCasale-Crouch, J, Turnbull, KLP, Colson, E, Kellams, A, Heeren, T, Kerr, S, Hauck, FR, Corwin, MJ. Investigating Mechanisms for Maternal Education Disparities in Enacting Health-Promoting Infant Care Practices. Acad Pediatr. 2020. 20:926-933. doi:10.1016/j.acap.2020.03.008. | Mediators/moderators; Intervention/exposure - KQ3
797 | Moore, AM, Smith, JJ, Stansfield, BK, Savage, JS, Lavner, JA. Patterns and Predictors of Breast Milk Feeding from Birth to Age 4 Months among Primiparous African American Mother-Infant Dyads. Nutrients. 2022. 14:2350. doi:10.3390/nu14112350. | Mediators/moderators; Intervention/exposure - KQ3
798 | Moraes, BA, Strada, JKR, Gasparin, VA, Espirito-Santo, LCD, Gouveia, HG, Gonçalves, AC. Breastfeeding in the first six months of life for babies seen by Lactation Consulting. Rev Lat Am Enfermagem. 2021. 29:e3412. doi:10.1590/1518-8345.3538.3412. | Country
799 | Mordini, B, Bortoli, E, Pagano, R, Barozzi, G, Ferrari, F. Correlations between welfare initiatives and breastfeeding rates: a 10-year follow-up study. Acta Paediatr. 2009. 98:80-5. doi:10.1111/j.1651-2227.2008.00986.x. | Country
800 | Morrell, E. First Food Justice: Infant Feeding Disparities and the First Food System. Breastfeed Med. 2017. 12:489-492. doi:10.1089/bfm.2017.0088. | Study design
801 | Morse, Holly. Changing the conversation around breastfeeding. Nursing Times. 2018. 114:1-1. | Country; Study design
802 | Mosley, EA, Pratt, M, Besera, G, Clarke, LS, Miller, H, Noland, T, Whaley, B, Cochran, J, Mack, A, Higgins, M. Evaluating Birth Outcomes From a Community-Based Pregnancy Support Program for Refugee Women in Georgia. Front Glob Womens Health. 2021. 2:655409. doi:10.3389/fgwh.2021.655409. | Outcome
803 | Moulton, KL, Battaglioli, N, Sebok-Syer, SS. Is Lactating in the Emergency Department a Letdown? Exploring Barriers and Supports to Workplace Lactation in Emergency Medicine. Ann Emerg Med. 2021. 78:400-408. doi:10.1016/j.annemergmed.2021.03.007. | Intervention/exposure - KQ3; Independent variable - KQ2
804 | Mrosková, S, Schlosserová, A, Reľovská, M. Analysis Of Selected Determinants Of Intention To Breastfeed. Central European Journal of Nursing & Midwifery. 2018. 9:939-946. doi:10.15452/CEJNM.2018.09.0027. | Country
805 | Mueffelmann, RE, Racine, EF, Warren-Findlow, J, Coffman, MJ. Perceived Infant Feeding Preferences of Significant Family Members and Mothers’ Intentions to Exclusively Breastfeed. J Hum Lact. 2015. 31:479-89. doi:10.1177/0890334414553941. | Outcome
806 | Mulder, P. Revision of the Beginning Breastfeeding Survey: a cumulative assessment of breastfeeding. J Nurs Meas. 2013. 21:80-95. doi:10.1891/1061-3749.21.1.80. | Intervention/exposure - KQ3; Independent variable - KQ2
807 | Mulder, PJ, Johnson, TS, Baker, LC. Excessive weight loss in breastfed infants during the postpartum hospitalization. J Obstet Gynecol Neonatal Nurs. 2010. 39:15-26. doi:10.1111/j.1552-6909.2009.01085.x. | Outcome
808 | Mulder, PJ, Johnson, TS. The Beginning Breastfeeding Survey: measuring mothers’ perceptions of breastfeeding effectiveness during the postpartum hospitalization. Res Nurs Health. 2010. 33:329-44. doi:10.1002/nur.20384. | Outcome
809 | Mullen, SM, Marshall, A, Warren, MD. Statewide Breastfeeding Hotline Use Among Tennessee WIC Participants. J Nutr Educ Behav. 2017. 49:S192-S196.e1. doi:10.1016/j.jneb.2017.04.024. | Mediators/moderators; Study participants
810 | Müller, FS, Silva, IA. Social representations about support for breastfeeding in a group of breastfeeding women. Revista Latino-Americana de Enfermagem (RLAE). 2009. 17:651-657. doi:10.1590/S0104-11692009000500009. | Country
811 | Mulready-Ward, C, Hackett, M. Perception and attitudes: breastfeeding in public in New York City. J Hum Lact. 2014. 30:195-200. doi:10.1177/0890334414524988. | Outcome
812 | Mulupuru, S, Siddu, A, Murki, S, Saikiran, D, Reddy, A. Breast crawl at birth, effect on breastfeeding rate and infant growth in infants delivered at an urban tertiary care public hospital: A randomized controlled trial. Journal of Neonatal Nursing. 2019. 25:236-239. doi:10.1016/j.jnn.2019.04.008. | Country
813 | Murimi, M, Dodge, CM, Pope, J, Erickson, D. Factors that influence breastfeeding decisions among special supplemental nutrition program for women, infants, and children participants from Central Louisiana. J Am Diet Assoc. 2010. 110:624-7. doi:10.1016/j.jada.2009.12.019. | Mediators/moderators; Intervention/exposure - KQ3
814 | Murphy, S. A perspective from Indian health service-supporting breastfeeding. Breastfeeding Medicine. 2011. 6:261-263. | Outcome
815 | Murtagh, L, Moulton, AD. Working mothers, breastfeeding, and the law. Am J Public Health. 2011. 101:217-23. doi:10.2105/ajph.2009.185280. | Independent variable - KQ2; Study participants
816 | Myers, D, Rubarth, LB. Facilitating breastfeeding in the neonatal intensive care unit: identifying barriers. Neonatal Network. 2013. 32:206-212. doi:10.1891/0730-0832.32.3.206. | Mediators/moderators; Intervention/exposure - KQ3; Study participants
817 | Nam Mi, Kang, Yoon Ji, Choi, Taisun, Hyun, Jung Eun, Lee. Associations of Breastfeeding Knowledge, Attitude and Interest with Breastfeeding Duration: A Cross-sectional Web-based Study. Journal of Korean Academy of Nursing. 2015. 45:449-458. doi:10.4040/jkan.2015.45.3.449. | Country
818 | Nelson, AM. Adolescent attitudes, beliefs, and concerns regarding breastfeeding. MCN Am J Matern Child Nurs. 2009. 34:249-55. doi:10.1097/01.Nmc.0000357918.18229.25. | Study participants
819 | Nelson, JM, Li, R, Perrine, CG, Scanlon, KS. Changes in mothers’ intended duration of breastfeeding from the prenatal to neonatal periods. Birth. 2018. 45:178-183. doi:10.1111/birt.12323. | Mediators/moderators; Intervention/exposure - KQ3
820 | Newman, HD, Carpenter, LM. Embodiment without bodies? Analysis of embodiment in US-based pro-breastfeeding and anti-male circumcision movements. Sociology of Health & Illness. 2014. 36:639-654. doi:10.1111/1467-9566.12095. | Study participants
821 | Newton, KN, Chaudhuri, J, Grossman, X, Merewood, A. Factors associated with exclusive breastfeeding among Latina women giving birth at an inner-city baby-friendly hospital. J Hum Lact. 2009. 25:28-33. doi:10.1177/0890334408329437. | Mediators/moderators; Intervention/exposure - KQ3
822 | Nguyen, MN, Siahpush, M, Grimm, BL, Singh, GK, Tibbits, MK. Women from racial or ethnic minority and low socioeconomic backgrounds receive more prenatal education: Results from the 2012 to 2014 Pregnancy Risk Assessment Monitoring System. Birth. 2019. 46:157-165. doi:10.1111/birt.12394. | Outcome
823 | Nichols, DD, Gaban, E, Wiseman, C, Schaedler, V, Gettel, V, Burnett, LL. Baby Friendly: A System’s Journey Through the ‘Ten Successful Steps to Breastfeeding’. JOGNN: Journal of Obstetric, Gynecologic & Neonatal Nursing. 2010. 39:S10-S10. doi:10.1111/j.1552-6909.2010.01117_5.x. | Publication status
824 | Nickel, NC, Taylor, EC, Labbok, MH, Weiner, BJ, Williamson, NE. Applying organisation theory to understand barriers and facilitators to the implementation of baby-friendly: A multisite qualitative study. Midwifery. 2013. 29:956-64. doi:10.1016/j.midw.2012.12.001. | Study participants
825 | Nnebe-Agumadu, UH, Racine, EF, Laditka, SB, Coffman, MJ. Associations between perceived value of exclusive breastfeeding among pregnant women in the United States and exclusive breastfeeding to three and six months postpartum: a prospective study. International Breastfeeding Journal. 2016. 11:10. doi:10.1186/s13006-016-0065-x. | Mediators/moderators; Intervention/exposure - KQ3
826 | Nobre, RS, Sousa, AF, Silva, Arvd, Machado, ALG, Silva, VMD, Lima, LHO. Construction and validation of educational material on promoting breastfeeding in schools. Rev Bras Enferm. 2021. 74:e20200511. doi:10.1590/0034-7167-2020-0511. | Country
827 | Nommsen-Rivers, LA, Chantry, CJ, Cohen, RJ, Dewey, KG. Comfort with the idea of formula feeding helps explain ethnic disparity in breastfeeding intentions among expectant first-time mothers. Breastfeed Med. 2010. 5:25-33. doi:10.1089/bfm.2009.0052. | Outcome
828 | Nommsen-Rivers, LA, Chantry, CJ, Peerson, JM, Cohen, RJ, Dewey, KG. Delayed onset of lactogenesis among first-time mothers is related to maternal obesity and factors associated with ineffective breastfeeding. American Journal of Clinical Nutrition. 2010. 92:574-584. doi:10.3945/ajcn.2010.29192. | Mediators/moderators; Intervention/exposure - KQ3
829 | Nommsen-Rivers, LA, Cohen, RJ, Chantry, CJ, Dewey, KG. The Infant Feeding Intentions scale demonstrates construct validity and comparability in quantifying maternal breastfeeding intentions across multiple ethnic groups. Matern Child Nutr. 2010. 6:220-7. doi:10.1111/j.1740-8709.2009.00213.x. | Mediators/moderators; Intervention/exposure - KQ3
830 | Nommsen-Rivers, LA, Dewey, KG. Development and validation of the Infant Feeding Intentions scale. Maternal & Child Health Journal. 2009. 13:334-342. doi:10.1007/s10995-008-0356-y. | Independent variable - KQ2; Study participants
831 | Noonan, MC, Rippeyoung, PLF. The economic costs of breastfeeding for women. Breastfeeding Medicine. 2011. 6:325-327. | Intervention/exposure - KQ3; Independent variable - KQ2
832 | Northrup, TF, Suchting, R, Green, C, Khan, A, Klawans, MR, Stotts, AL. Duration of breastmilk feeding of NICU graduates who live with individuals who smoke. Pediatr Res. 2021. 89:1788-1797. doi:10.1038/s41390-020-01150-6. | Mediators/moderators; Intervention/exposure - KQ3
833 | Nouer, SS, Ware, JL, Baldwin, KM, Hare, ME. Changes in Breastfeeding Attitudes in a Metropolitan Community in Tennessee. J Hum Lact. 2015. 31:519-29. doi:10.1177/0890334415578648. | Mediators/moderators; Intervention/exposure - KQ3
834 | Noviani, M, Wasserman, S, Clowse, ME. Breastfeeding in mothers with systemic lupus erythematosus. Lupus. 2016. 25:973-9. doi:10.1177/0961203316629555. | Mediators/moderators; Intervention/exposure - KQ3
835 | Nunes, RD, Puel, AG, Gomes, N, Traebert, J. Evaluating the effectiveness of an educative workshop for pregnant women using pre and post intervention surveys. Cad Saude Publica. 2019. 35:e00155018. doi:10.1590/0102-311x00155018. | Country
836 | Nyange, C. Promoting Breastfeeding in African-American Women. International Journal of Childbirth Education. 2018. 33:14-16. | Study design
837 | Obaid, M, Igawa, T, Maxwell, A, Murray, YL, Rahman, A, Aboudi, D, Olivo, K, Roeder, T, Valdes-Greene, R, Brumberg, H, Alpan, G, Parvez, B. “Liquid Gold” Lactation Bundle and Breastfeeding Rates in Racially Diverse Mothers of Extremely Low-Birth-Weight Infants. Breastfeed Med. 2021. 16:463-470. doi:10.1089/bfm.2020.0322. | Study participants
838 | Obeng, C, Dickinson, S, Golzarri-Arroyo, L. Women’s Perceptions about Breastfeeding: A Preliminary Study. Children (Basel). 2020. 7:61. doi:10.3390/children7060061. | Mediators/moderators; Intervention/exposure - KQ3
839 | O’Connor, AB, Collett, A, Alto, WA, O’Brien, LM. Breastfeeding Rates and the Relationship Between Breastfeeding and Neonatal Abstinence Syndrome in Women Maintained on Buprenorphine During Pregnancy. Journal of Midwifery & Women’s Health. 2013. 58:383-388. doi:10.1111/jmwh.12009. | Independent variable - KQ2; Study participants
840 | O’Connor, M, Allen, J, Kelly, J, Gao, Y, Kildea, S. Predictors of breastfeeding exclusivity and duration in a hospital without Baby Friendly Hospital Initiative accreditation: A prospective cohort study. Women Birth. 2018. 31:319-324. doi:10.1016/j.wombi.2017.10.013. | Country
841 | Odar Stough, C, Khalsa, AS, Nabors, LA, Merianos, AL, Peugh, J. Predictors of Exclusive Breastfeeding for 6 Months in a National Sample of US Children. Am J Health Promot. 2019. 33:48-56. doi:10.1177/0890117118774208. | Mediators/moderators; Intervention/exposure - KQ3
842 | Oddy, WH, Smith, GJ, Jacoby, P. A possible strategy for developing a model to account for attrition bias in a longitudinal cohort to investigate associations between exclusive breastfeeding and overweight and obesity at 20 years. Ann Nutr Metab. 2014. 65:234-5. doi:10.1159/000360548. | Country
843 | Odom, EC, Li, R, Scanlon, KS, Perrine, CG, Grummer-Strawn, L. Association of family and health care provider opinion on infant feeding with mother’s breastfeeding decision. J Acad Nutr Diet. 2014. 114:1203-7. doi:10.1016/j.jand.2013.08.001. | Mediators/moderators; Intervention/exposure - KQ3
844 | Ogbuanu, CA, Probst, J, Laditka, SB, Liu, J, Baek, J, Glover, S. Reasons why women do not initiate breastfeeding: A southeastern state study. Womens Health Issues. 2009. 19:268-78. doi:10.1016/j.whi.2009.03.005. | Mediators/moderators; Intervention/exposure - KQ3
845 | Ogbuanu, C, Glover, S, Probst, J, Hussey, J, Liu, J. Balancing Work and Family: Effect of Employment Characteristics on Breastfeeding. Journal of Human Lactation. 2011. 27:225-238. doi:10.1177/0890334410394860. | Mediators/moderators; Intervention/exposure - KQ3
846 | Ogg, S, Klosky, JL, Chemaitilly, W, Srivastava, DK, Wang, M, Carney, G, Ojha, R, Robison, LL, Cox, CL, Hudson, MM. Breastfeeding practices among childhood cancer survivors. J Cancer Surviv. 2020. 14:586-599. doi:10.1007/s11764-020-00882-y. | Intervention/exposure - KQ3; Independent variable - KQ2
847 | Ogunwale, AN, Anderson, ML, Sangi-Haghpeykar, H. Intimate Partner Violence During Pregnancy and Maternal and Neonatal Health Among Hispanic Women. Journal of Reproductive Medicine. 2017. 62:65-71. | Intervention/exposure - KQ3; Comparator - KQ2
848 | O’Hara, MH, Frazier, LM, Stembridge, TW, McKay, RS, Mohr, SN, Shalat, SL. Physician-Led, Hospital-Linked, Birth Care Centers can Decrease Cesarean Section Rates Without Increasing Rates of Adverse Events. Birth: Issues in Perinatal Care. 2013. 40:155-163. doi:10.1111/birt.12051. | Independent variable - KQ2; Study participants
849 | Oliver, S, Petty, J. Breast-feeding and HIV transmission: An analysis of the factors influencing HIV positive mothers decision to breast-feed - A case study approach. Journal of Neonatal Nursing. 2012. 18:155-162. | Country; Study design
850 | Olson, BH, Haider, SJ, Vangjel, L, Bolton, TA, Gold, JG. A quasi-experimental evaluation of a breastfeeding support program for low income women in Michigan. Matern Child Health J. 2010. 14:86-93. doi:10.1007/s10995-008-0430-5. | Mediators/moderators; Study participants
851 | Olson, BH, Sigman-Grant, M, Braun, MT. Workplace Lactation Support: Using Implementation Climate to Inform a New Model. Breastfeed Med. 2020. 15:417-422. doi:10.1089/bfm.2020.0037. | Intervention/exposure - KQ3; Outcome; Study participants
852 | Omekara, FU. Hand Expression With Lactation Support: Effect on Self-Efficacy and Breastfeeding Duration. Walden University; 2018. | Publication status
853 | Onat, G, Karakoç, H. Three spirals: Breastfeeding problems, growth spurts, and postpartum depression. Perspectives in Psychiatric Care. 2021. 57:770-776. doi:10.1111/ppc.12612. | Country
854 | Oniwon, O, Tender, JA, He, J, Voorhees, E, Moon, RY. Reasons for Infant Feeding Decisions in Low-Income Families in Washington, DC. J Hum Lact. 2016. 32:704-710. doi:10.1177/0890334416653739. | Mediators/moderators; Intervention/exposure - KQ3
855 | Oras, P, Ljungberg, T, Hellström-Westas, L, Funkquist, EL. A breastfeeding support program changed breastfeeding patterns but did not affect the mothers’ self-efficacy in breastfeeding at two months. Early Hum Dev. 2020. 151:105242. doi:10.1016/j.earlhumdev.2020.105242. | Country
856 | Ortiz-Félix, RE, Cárdenas-Villarreal, VM, Miranda-Félix, PE, Guevara-Valtier, MC. Impact of a prenatal education intervention in pregnant women to prevent overweight in infants. Gac Med Mex. 2021. 157:3-9. doi:10.24875/gmm.M21000529. | Country
857 | Otarola, L, Sly, J, Manigat, T, Shapiro, J, Wetmore, J, Torres, M, Jandorf, L. Understanding Black Matriarchal Role Models in the U.S. Attitudes and Beliefs About Breastfeeding. Breastfeed Med. 2021. 16:501-505. doi:10.1089/bfm.2020.0320. | Outcome
858 | Ouyang, YQ, Xu, YX, Zhang, Q. Survey on breastfeeding among Chinese female physicians and nurses. Nurs Health Sci. 2012. 14:298-303. doi:10.1111/j.1442-2018.2012.00699.x. | Country
859 | Oza-Frank, R, Chertok, I, Bartley, A. Differences in breast-feeding initiation and continuation by maternal diabetes status. Public Health Nutr. 2015. 18:727-35. doi:10.1017/s1368980014000792. | Mediators/moderators; Intervention/exposure - KQ3
860 | Oza-Frank, R, Moreland, JJ, McNamara, K, Geraghty, SR, Keim, SA. Early Lactation and Infant Feeding Practices Differ by Maternal Gestational Diabetes History. J Hum Lact. 2016. 32:658-665. doi:10.1177/0890334416663196. | Mediators/moderators; Intervention/exposure - KQ3
861 | Paddock, JD. Breastfeeding Patterns Among Employees at a Land Grant University. Workplace Health Saf. 2017. 65:580-594. doi:10.1177/2165079917701138. | Mediators/moderators; Intervention/exposure - KQ3
862 | Paes Pedras, CT, Mezzacappa, MA, da Costa-Pinto, EA. Breastfeeding of very low-weight infants before and after implementation of the baby-friendly hospital initiative. Journal of Tropical Pediatrics. 2012. 58:324-326. doi:10.1093/tropej/fmr075. | Country
863 | Paglia, L. Taste development and prenatal prevention. Eur J Paediatr Dent. 2019. 20:257. doi:10.23804/ejpd.2019.20.04.01. | Outcome
864 | Palmer, JR, Kipping-Ruane, K, Wise, LA, Yu, J, Rosenberg, L. Lactation in Relation to Long-Term Maternal Weight Gain in African-American Women. Am J Epidemiol. 2015. 181:932-9. doi:10.1093/aje/kwv027. | Outcome
865 | Palmer, L, Cook, A, Courtot, B. Comparing models of maternity care serving women at risk of poor birth outcomes in Washington, DC. Altern Ther Health Med. 2010. 16:48-56. | Outcome
866 | Palmér, L, Gustafsson, I. A Theoretical Model on Caring for Mothers With Initial Breastfeeding Difficulties: The Breastfeeding Story as a Hub for Caring Practice. International Journal for Human Caring. 2021. 25:45-59. doi:10.20467/HumanCaring-D-19-00056. | Country
867 | Palmer, M. Preconception subsidized insurance: Prenatal care and birth outcomes by race/ethnicity. Health Econ. 2020. 29:1013-1030. doi:10.1002/hec.4116. | Study design
868 | Palmquist, AEL, Holdren, SM, Fair, CD. “It was all taken away”: Lactation, embodiment, and resistance among mothers caring for their very-low-birth-weight infants in the neonatal intensive care unit. Social Science & Medicine. 2020. 244:N.PAG-N.PAG. doi:10.1016/j.socscimed.2019.112648. | Intervention/exposure - KQ3; Independent variable - KQ2; Study participants
869 | Paolicelli, C, Berman, D, Owens, T, Magness, A, Scanlon, KS. Breastfeeding and Complementary Feeding Patterns Among Women Enrolled in WIC: WIC Infant and Toddler Feeding Practices Study-2. Breastfeed Med. 2017. 12:482-486. doi:10.1089/bfm.2017.0118. | Intervention/exposure - KQ3; Independent variable - KQ2
870 | Papa, J, Agostinelli, J, Rodriguez, G, Robinson, D. Implementation of Best Practices in Obesity Prevention in Child Care Facilities: The Arizona Empower Program, 2013-2015. Prev Chronic Dis. 2017. 14:E75. doi:10.5888/pcd14.160451. | Outcome
871 | Park, Seungmi, Jang, In Sun, Min, Deulle. Factors Associated with the Need for Breastfeeding Information Among Women with Gestational Diabetes Mellitus: A Cross-sectional Study. Asian Nursing Research. 2021. 15:210-214. doi:10.1016/j.anr.2021.05.002. | Country
872 | Parker, LA, Krueger, C, Sullivan, S, Mueller, M. Demographic, Social, and Personal Factors Associated With Lactation Cessation by 6 Weeks in Mothers of Very Low Birth Weight Infants. J Hum Lact. 2021. 37:511-520. doi:10.1177/0890334420940239. | Mediators/moderators; Intervention/exposure - KQ3
873 | Parker, MG, Burnham, L, Mao, W, Philipp, BL, Merewood, A. Implementation of a Donor Milk Program Is Associated with Greater Consumption of Mothers’ Own Milk among VLBW Infants in a US, Level 3 NICU. J Hum Lact. 2016. 32:221-8. doi:10.1177/0890334415598305. | Study participants
874 | Parker, MG, Burnham, LA, Melvin, P, Singh, R, Lopera, AM, Belfort, MB, Moses, JM, Gupta, M. Addressing Disparities in Mother’s Milk for VLBW Infants Through Statewide Quality Improvement. Pediatrics. 2019. 144: e20183809. doi:10.1542/peds.2018-3809. | Mediators/moderators; Study participants
875 | Parker, MG, Greenberg, LT, Edwards, EM, Ehret, D, Belfort, MB, Horbar, JD. National Trends in the Provision of Human Milk at Hospital Discharge Among Very Low-Birth-Weight Infants. JAMA Pediatr. 2019. 173:961-968. doi:10.1001/jamapediatrics.2019.2645. | Study Participants
876 | Parker, MG, Gupta, M, Melvin, P, Burnham, LA, Lopera, AM, Moses, JM, Litt, JS, Belfort, MB. Racial and Ethnic Disparities in the Use of Mother’s Milk Feeding for Very Low Birth Weight Infants in Massachusetts. J Pediatr. 2019. 204:134-141.e1. doi:10.1016/j.jpeds.2018.08.036. | Study Participants
877 | Parker, MG, Hwang, SS, Forbes, ES, Colvin, BN, Brown, KR, Colson, ER. Use of the Theory of Planned Behavior Framework to Understand Breastfeeding Decision-Making Among Mothers of Preterm Infants. Breastfeed Med. 2020. 15:608-615. doi:10.1089/bfm.2020.0127. | Intervention/exposure - KQ3; Study participants
878 | Parker, MG, Lopera, AM, Kalluri, NS, Kistin, CJ. “I Felt Like I Was a Part of Trying to Keep My Baby Alive”: Perspectives of Hispanic and Non-Hispanic Black Mothers in Providing Milk for Their Very Preterm Infants. Breastfeed Med. 2018. 13:657-665. doi:10.1089/bfm.2018.0104. | Intervention/exposure - KQ3; Study participants
879 | Parker, MGK, Colson, ER, Provini, L, Rybin, DV, Kerr, SM, Heeren, T, Corwin, MJ. Variation in Safe Sleep and Breastfeeding Practices Among Non-Hispanic Black Mothers in the United States According to Birth Country. Acad Pediatr. 2017. 17:887-892. doi:10.1016/j.acap.2017.07.003. | Intervention/exposure - KQ3; Independent variable - KQ2
880 | Parry, JE, Ip, DKM, Chau, PYK, Wu, KM, Tarrant, Marie. Predictors and Consequences of In-Hospital Formula Supplementation for Healthy Breastfeeding Newborns. Journal of Human Lactation. 2013. 29:527-536. doi:10.1177/0890334412474719. | Country
881 | Patchen, L, Ellis, L, Harrington, CB, Ma, T, Mohanraj, R, Andrews, V, Evans, WD. Engaging African American Parents to Develop a Mobile Health Technology for Breastfeeding: KULEA-NET. J Hum Lact. 2020. 36:448-460. doi:10.1177/0890334420930208. | Outcome
882 | Pate, BL. Effectiveness of Web-based programs in improving breastfeeding self-efficacy. University of Arkansas for Medical Sciences; 2009. | Publication status
883 | Patel, AL, Schoeny, ME, Hoban, R, Johnson, TJ, Bigger, H, Engstrom, JL, Fleurant, E, Riley, B, Meier, PP. Mediators of racial and ethnic disparity in mother’s own milk feeding in very low birth weight infants. Pediatr Res. 2019. 85:662-670. doi:10.1038/s41390-019-0290-2. | Study Participants
884 | Patel, AL, Johnson, TJ, Meier, PP. Racial and socioeconomic disparities in breast milk feedings in US neonatal intensive care units. Pediatric Research. 2021. 89:344-352. doi:10.1038/s41390-020-01263-y. | Study design
885 | Paterno, MT, Jablonski, L, Klepacki, A, Friedmann, PD. Evaluation of a Nurse-Led Program for Rural Pregnant Women With Opioid Use Disorder to Improve Maternal–Neonatal Outcomes. JOGNN: Journal of Obstetric, Gynecologic & Neonatal Nursing. 2019. 48:495-506. doi:10.1016/j.jogn.2019.07.002. | Mediators/moderators; Study participants
886 | Patterson, JA, Keuler, NS, Buckingham, WR. Differences in Exclusive Breastfeeding Rates in US Hospitals According to Baby-Friendly Hospital Initiative Designation and Area Deprivation Index Category. Breastfeed Med. 2021. 16:799-806. doi:10.1089/bfm.2021.0050. | Independent variable - KQ2; Study participants
887 | Patterson, JA, Keuler, NS, Olson, BH. The effect of Baby-friendly status on exclusive breastfeeding in U.S. hospitals. Matern Child Nutr. 2018. 14:e12589. doi:10.1111/mcn.12589. | Mediators/moderators; Study participants
888 | Payne, D, Nicholls, DA. Managing breastfeeding and work: a Foucauldian secondary analysis. J Adv Nurs. 2010. 66:1810-8. doi:10.1111/j.1365-2648.2009.05156.x. | Country
889 | Pearsall, MS, Stuebe, AM, Seashore, C, Sullivan, C, Tully, KP. Welcoming, supportive care in US birthing facilities and realization of breastfeeding goals. Midwifery. 2022. 111:103359. doi:10.1016/j.midw.2022.103359. | Intervention/exposure - KQ3; Independent variable - KQ2; Study participants
890 | Pearson, ACS, Dodd, SE, Kraus, MB, Ondecko Ligda, KM, Hertzberg, LB, Patel, PV, Chandrabose, RK. Pilot Survey of Female Anesthesiologists’ Childbearing and Parental Leave Experiences. Anesth Analg. 2019. 128:e109-e112. doi:10.1213/ane.0000000000003802. | Study participants
891 | Pellechia, K, Soto, V, Haake, M, Schneider, J. Development and Implementation of a Loving Support Makes Breastfeeding Work Social Media Toolkit for WIC Staff. J Nutr Educ Behav. 2017. 49:S212-S213.e1. doi:10.1016/j.jneb.2017.03.022. | Outcome
892 | Pellegrinelli, ALR, Pereira, SCL, Ribeiro, IP, dos Santos, LC. Influence of pacifier use and bottle in exclusive breastfeeding among mothers treated at a Human Milk Bank. Revista De Nutricao-Brazilian Journal of Nutrition. 2015. 28:631-639. doi:10.1590/1415-52732015000600006. | Country; Language
893 | Penwell, A. Breastfeeding and newborn survival. Midwifery Today Int Midwife. 2012. 51-3. | Country
894 | Perdion, K, Lesser, R, Hirsch, J, Barger, M, Kelly, TF, Moore, TR, Lacoursiere, YD. A Midwifery-Led In-Hospital Birth Center Within an Academic Medical Center. Journal of Perinatal & Neonatal Nursing. 2013. 27:302-310. doi:10.1097/jpn.0b013e3182a3cd42. | Comparator
895 | Pereira da Silva Rocha, FN, de Barros Patrício, F, Souza dos Passos, MN, Oliveira de Lima, SW, Santos Nunes, MG. Characterization Of The Puerperal Women’s Knowledge About Breastfeeding. Journal of Nursing UFPE / Revista de Enfermagem UFPE. 2018. 12:2386-2392. doi:10.5205/1981-8963-v12i9a235911p2386-2392-2018. | Country
896 | Pereira de Souza, FL, Matozinhos Clark, L, Brazão Lelis, BD, de Sousa Dusso, MI, Moraes Leite, A. Feelings And Meanings: Hiv In The Impossibility Of Breastfeeding. Journal of Nursing UFPE / Revista de Enfermagem UFPE. 2019. 13:1055-1060. doi:10.5205/1981-8963.2019.241854. | Country
897 | Pérez-Escamilla, R, Sellen, D. Equity in Breastfeeding: Where Do We Go from Here?. Journal of Human Lactation. 2015. 31:12-14. doi:10.1177/0890334414561062. | Study design
898 | Peripolli Rodrigues, A, de Mello Padoin, SM, Cardoso de Paula, C, de Oliveira Souza, ÍE, de Almeida, PC, Barbosa Ximenes, L. Influence of sociodemographic and behavioral conditions on self-efficacy in breastfeeding: a cross-sectional study. Online Brazilian Journal of Nursing. 2015. 14:1-7. | Country
899 | Perrin, EM, Rothman, RL, Sanders, LM, Skinner, AC, Eden, SK, Shintani, A, Throop, EM, Yin, HS. Racial and ethnic differences associated with feeding- and activity-related behaviors in infants. Pediatrics. 2014. 133:e857-67. doi:10.1542/peds.2013-1326. | Outcome
900 | Pesch, MH, Tomlinson, S, Singer, K, Burrows, HL. Pediatricians Advocating Breastfeeding: Let’s Start with Supporting our Fellow Pediatricians First. Journal of Pediatrics. 2019. 206:6-7. doi:10.1016/j.jpeds.2018.12.057. | Outcome
901 | Phelan, S, Smith, K, Steele, J, Wilt, D, Ames, S, McClure, L. What type of weight loss program do postpartum women want? Treatment preferences of postpartum women in two community settings. Californian Journal of Health Promotion. 2010. 8:22-31. doi:10.32398/cjhp.v8i1.2027. | Study participants
902 | Phelps, CE. Economic issues of breastfeeding. Breastfeed Med. 2011. 6:307-11. doi:10.1089/bfm.2011.0062. | Study design
903 | Phelps, CE. Economics of healthcare financing: implications for breastfeeding. Breastfeeding Medicine. 2010. 5:191-199. doi:10.1089/bfm.2010.0041. | Study design
904 | Phillips, G, Brett, K, Mendola, P. Previous Breastfeeding Practices and Duration of Exclusive Breastfeeding in the United States. Maternal & Child Health Journal. 2011. 15:1210-1216. doi:10.1007/s10995-010-0694-4. | Mediators/moderators; Intervention/exposure - KQ3
905 | Phillips, R, Copeland, L, Grant, A, Sanders, J, Gobat, N, Tedstone, S, Stanton, H, Merrett, L, Rollnick, S, Robling, M, Brown, A, Hunter, B, Fitzsimmons, D, Regan, S, Trickey, H, Paranjothy, S. Development of a novel motivational interviewing (MI) informed peer-support intervention to support mothers to breastfeed for longer. Bmc Pregnancy and Childbirth. 2018. 18:14. doi:10.1186/s12884-018-1725-1. | Country
906 | Phipps, AI, Li, CI. Breastfeeding and triple-negative breast cancer: potential implications for racial/ethnic disparities. JNCI: Journal of the National Cancer Institute. 2014. 106:dju281-dju281. doi:10.1093/jnci/dju281. | Study design
907 | Pierro, J, Abulaimoun, B, Roth, P, Blau, J. Factors Associated with Supplemental Formula Feeding of Breastfeeding Infants During Postpartum Hospital Stay. Breastfeed Med. 2016. 11:196-202. doi:10.1089/bfm.2015.0091. | Mediators/moderators; Intervention/exposure - KQ3
908 | Pihl, AM, Basso, G. Did California Paid Family Leave Impact Infant Health?. J Policy Anal Manage. 2019. 38:155-80. | Mediators/moderators; Study participants
909 | Pilkauskas, NV. Breastfeeding initiation and duration in coresident grandparent, mother and infant households. Matern Child Health J. 2014. 18:1955-63. doi:10.1007/s10995-014-1441-z. | Mediators/moderators; Intervention/exposure - KQ3
910 | Pilkington, M, Alshaikh, BN, Brindle, MaryE. Human Milk Fortification for Preterm Infants: The Right Kind at the Right Time for the Right Baby. JAMA Pediatrics. 2021. 175:777-778. doi:10.1001/jamapediatrics.2021.0689. | Study design
911 | Pineda, R, Luong, A, Ryckman, J, Smith, J. Pacifier use in newborns: related to socioeconomic status but not to early feeding performance. Acta Paediatr. 2018. 107:806-810. doi:10.1111/apa.14253. | Intervention/exposure - KQ3; Independent variable - KQ2
912 | Pineda, R, Muñoz, R, Chrzastowski, H, Dunsirn-Baillie, S, Wallendorf, M, Smith, J. Maternal Milk and Relationships to Early Neurobehavioral Outcome in Preterm Infants. J Perinat Neonatal Nurs. 2020. 34:72-79. doi:10.1097/jpn.0000000000000460. | Mediators/moderators; Intervention/exposure - KQ3
913 | Pineda, RG, Foss, J, Richards, L, Pane, CA. Breastfeeding changes for VLBW infants in the NICU following staff education. Neonatal Netw. 2009. 28:311-9. doi:10.1891/0730-0832.28.5.311. | Study participants
914 | Pineda, RG. Predictors of breastfeeding and breastmilk feeding among very low birth weight infants. Breastfeed Med. 2011. 6:15-9. doi:10.1089/bfm.2010.0010. | Mediators/moderators; Intervention/exposure - KQ3
915 | Pineros-Leano, M, Tabb, KM, Simonovich, SD, Wang, Y, Meline, B, Huang, H. Racial Differences in Breastfeeding Initiation Among Participants in a Midwestern Public Health District. Health Equity. 2018. 2:296-303. doi:10.1089/heq.2018.0016. | Mediators/moderators; Intervention/exposure - KQ3
916 | Pinheiro de Oliveira, PM, Rodrigues Faria de Carvalho, A L, Freitag Pagliuca, LM. Cultural Adaptation Of Educative Technology In Health: String Literature With A Focus On Breastfeeding. Texto & Contexto Enfermagem. 2014. 23:134-141. | Country
917 | Pinkney, K. The practice and attitudes of gypsy and traveller women towards early infant feeding. Community Practitioner. 2012. 85:26-29. | Country
918 | Piperata, BA. Variation in maternal strategies during lactation: the role of the biosocial context. Am J Hum Biol. 2009. 21:817-27. doi:10.1002/ajhb.20898. | Country
919 | Pitcock, N. Evaluation of an Initiative to Increase Rates of Exclusive Breastfeeding Among Rural Hispanic Immigrant Women. University of Virginia; 2013. | Publication status
920 | Pitonyak, JS, Mroz, TM, Fogelberg, D. Expanding client-centred thinking to include social determinants: a practical scenario based on the occupation of breastfeeding. Scandinavian Journal of Occupational Therapy. 2015. 22:277-282. doi:10.3109/11038128.2015.1020865. | Independent variable - KQ2; Study participants
921 | Pitonyak, JS, Jessop, AB, Pontiggia, L, Crivelli-Kovach, A. Life Course Factors Associated with Initiation and Continuation of Exclusive Breastfeeding. Matern Child Health J. 2016. 20:240-9. doi:10.1007/s10995-015-1823-x. | Mediators/moderators; Intervention/exposure - KQ3
922 | Plested, M. Breastfeeding barriers: is there room for lactating midwives?. Essentially MIDIRS. 2014. 5:34-37. | Study design
923 | Polido, CG, de Mello, DF, Parada, Cmgd, Carvalhaes, Mabl, Tonete, VLP. Maternal experiences associated with longer term exclusive breastfeeding: an ethnographic study. Acta Paulista De Enfermagem. 2011. 24:624-630. doi:10.1590/s0103-21002011000500005. | Country; Language
924 | Pollard, D, Guill, M. The relationship between baseline self-efficacy and breastfeeding duration. Southern Online Journal of Nursing Research. 2009. 9:8p-8p. | Mediators/moderators; Intervention/exposure - KQ3
925 | Pollard, DL. Impact of a feeding log on breastfeeding duration and exclusivity. Matern Child Health J. 2011. 15:395-400. doi:10.1007/s10995-010-0583-x. | Mediators/moderators; Study participants
926 | Pontoppidan, M, Nygaard, L, Thorsager, M, Friis-Hansen, M, Davis, D, Nohr, EA. The FACAM study: protocol for a randomized controlled study of an early interdisciplinary intervention to support women in vulnerable positions through pregnancy and the first 5 years of motherhood. Trials. 2022. 23:14. doi:10.1186/s13063-022-06022-4. | Country
927 | Poorman, E, Gazmararian, J, Elon, L, Parker, R. Is health literacy related to health behaviors and cell phone usage patterns among the text4baby target population?. Arch Public Health. 2014. 72:13. doi:10.1186/2049-3258-72-13. | Outcome
928 | Pounds, L, Fisher, CM, Barnes-Josiah, D, Coleman, JD, Lefebvre, RC. The Role of Early Maternal Support in Balancing Full-Time Work and Infant Exclusive Breastfeeding: A Qualitative Study. Breastfeed Med. 2017. 12:33-38. doi:10.1089/bfm.2016.0151. | Study participants
929 | Powell, K. Why scientist-mums in the United States need better parental-support policies. Nature. 2019. 569:149-151. doi:10.1038/d41586-019-01315-2. | Study design
930 | Prado, B, McMahan, S, Mouttapa, M, Salazar, I, Love, G, Norwood, S. An Educational Telenovela (Soap Opera) Approach to Promote Breastfeeding Among U.S. Latinas. Californian Journal of Health Promotion. 2012. 10:67-73. | Outcome
931 | Pratt, BA, Longo, J, Gordon, SC, Jones, Nancy Aaron. Perceptions of Breastfeeding for Women with Perinatal Depression: A Descriptive Phenomenological Study. Issues in Mental Health Nursing. 2020. 41:637-644. doi:10.1080/01612840.2019.1691690. | Independent variable - KQ2; Study participants
932 | Pratt, BA. The Lived Experience of Breastfeeding for Women with Perinatal Depression. Florida Atlantic University; 2017. | Publication status
933 | Preece, H, Hawn, C. The Story of “KINDNESS” From Rural Alaska: A Model for Comprehensive Infant Feeding Support. Clinical Lactation. 2019. 10:164-174. doi:10.1891/2158-0782.10.4.164. | Mediators/moderators; Comparator; Study participants
934 | Price, SN, McDonald, J, Oken, E, Haines, J, Gillman, MW, Taveras, EM. Content analysis of motivational counseling calls targeting obesity-related behaviors among postpartum women. Matern Child Health J. 2012. 16:439-47. doi:10.1007/s10995-011-0746-4. | Study participants
935 | Provini, LE, Corwin, MJ, Geller, NL, Heeren, TC, Moon, RY, Rybin, DV, Shapiro-Mendoza, CK, Colson, ER. Differences in Infant Care Practices and Smoking among Hispanic Mothers Living in the United States. J Pediatr. 2017. 182:321-326.e1. doi:10.1016/j.jpeds.2016.11.053. | Mediators/moderators; Intervention/exposure - KQ3
936 | Purdy, IB. Social, cultural, and medical factors that influence maternal breastfeeding. Issues Ment Health Nurs. 2010. 31:365-7. doi:10.3109/01612840903359757. | Study design
937 | Pyles, TEH, Umi, SA, Madubuonwu, S, Stiles, A, Devane-Johnson, S, Scott, H, Rhoads, S, Russell, JH. Breastfeeding Sisters That Are Receiving Support: Community-Based Peer Support Program Created for and by Women of Color. Breastfeed Med. 2021. 16:165-170. doi:10.1089/bfm.2020.0313. | Outcome
938 | Quigley, MA. Breast feeding, causal effects and inequalities. Archives of Disease in Childhood. 2013. 98:654-655. doi:10.1136/archdischild-2013-304188. | Study design
939 | Quilton, K. ‘We don’t see breastfeeding in public, we don’t see it in the media’. Midwives. 2018. 21:21-23. | Country; Independent variable - KQ2; Study participants
940 | Rabin, JM, Weinstein, ED, Seltzer, VL, Langer, M, Kohn, N. Benefits of a comprehensive, publicly funded prenatal care and obstetrics program. J Reprod Med. 2009. 54:533-40. | Independent variable - KQ2; Study participants
941 | Racial Disparities Remain in Breastfeeding Rates. Jama. 2017. 318:691. doi:10.1001/jama.2017.10454. | Mediators/moderators; Intervention/exposure - KQ3
942 | Racial Disparity in Breastfeeding. Jama-Journal of the American Medical Association. 2014. 312:1730-1730. doi:10.1001/jama.2014.13706. | Study design; Publication status
943 | Racine, EF, Frick, K, Guthrie, JF, Strobino, D. Individual net-benefit maximization: a model for understanding breastfeeding cessation among low-income women. Matern Child Health J. 2009. 13:241-9. doi:10.1007/s10995-008-0337-1. | Mediators/moderators; Intervention/exposure - KQ3
944 | Radwan, Catherine. WIC program cuts infants’ risk for early death and preterm birth. Contemporary Pediatrics. 2020. 37:20-21. | Study design
945 | Radzyminski, S, Callister, LC. Mother’s Beliefs, Attitudes, and Decision Making Related to Infant Feeding Choices. J Perinat Educ. 2016. 25:18-28. doi:10.1891/1058-1243.25.1.18. | Study participants
946 | Rajegowda, BK, Aslam, M. WIC vs breastfeeding. Neonatal Intensive Care. 2009. 22:13-14. | Publication status
947 | Ram, S, Ram, HS, Rosenthal, YS, Attali, E, Warshaviak, M, Gamzu, R, Yogev, Y, Chodick, G. The impact of breast augmentation on breast feeding in primigravida women - A cohort study. Eur J Obstet Gynecol Reprod Biol. 2022. 268:116-120. doi:10.1016/j.ejogrb.2021.11.436. | Country
948 | Ramos, DE. Breastfeeding: A Bridge to Addressing Disparities in Obesity and Health. Breastfeeding Medicine. 2012. 7:354-357. doi:10.1089/bfm.2012.0076. | Study design
949 | Ramsey, KW, Beckwith, N, Heathcock, L, Myers, T, Balaraman, V. Advocating For a Culture of Support for Lactating Medical Residents in Hawai’i. Hawaii J Health Soc Welf. 2021. 80:304-306. | Independent variable - KQ2; Outcome; Study participants
950 | Rasmussen, KM, Dieterich, CM, Zelek, ST, Altabet, JD, Kjolhede, CL. Interventions to Increase the Duration of Breastfeeding in Obese Mothers: The Bassett Improving Breastfeeding Study. Breastfeeding Medicine. 2011. 6:69-75. doi:10.1089/bfm.2010.0014. | Independent variable - KQ2; Study participants
951 | Ray, R. Analysis of Pregnancy Anti-Discrimination Policy in Kentucky: Application of Kingdon’s Multiple Streams Framework. Policy Polit Nurs Pract. 2020. 21:244-253. doi:10.1177/1527154420957303. | Outcome
952 | Reat, A, Matthews, KJ, Carver, AE, Perez, CA, Stagg, J, Byrd-Williams, CE. Support for Breastfeeding Employees: Assessing Statewide Worksite Lactation Support Recognition Initiatives in the United States. J Hum Lact. 2020. 36:328-336. doi:10.1177/0890334419865902. | Outcome; Study participants
953 | Reeves, EA, Woods-Giscombé, CL. Infant-feeding practices among African American women: social-ecological analysis and implications for practice. J Transcult Nurs. 2015. 26:219-26. doi:10.1177/1043659614526244. | Study design
954 | Regan, J, Thompson, A, DeFranco, E. The influence of mode of delivery on breastfeeding initiation in women with a prior cesarean delivery: a population-based study. Breastfeed Med. 2013. 8:181-6. doi:10.1089/bfm.2012.0049. | Mediators/moderators; Intervention/exposure - KQ3
955 | Rei, Y, Rasmussen, KM, Felice, JP, Yamada, R. “What Is ‘Enough,’ and How Do I Make It?”: A Qualitative Examination of Questions Mothers Ask on Social Media About Pumping and Providing an Adequate Amount of Milk for Their Infants. Breastfeeding Medicine. 2019. 14:17-21. doi:10.1089/bfm.2018.0154. | Study participants
956 | Reifsnider, E, Flowers, J, Todd, M, Bever Babendure, J, Moramarco, M. The Relationship Among Breastfeeding, Postpartum Depression, and Postpartum Weight in Mexican American Women. J Obstet Gynecol Neonatal Nurs. 2016. 45:760-771. doi:10.1016/j.jogn.2016.05.009. | Mediators/moderators; Intervention/exposure - KQ3
957 | Reilly, G, Tipton, C, Liberman, P, Berkenstock, M. Attitudes toward parental leave and breastfeeding during ophthalmology residency. Can J Ophthalmol. 2022. 57:175-187. doi:10.1016/j.jcjo.2021.02.039. | Mediators/moderators; Study participants
958 | Reilly, KH, Zimmerman, R, Huynh, M, Kennedy, J, McVeigh, KH. Characteristics of Mothers and Infants Living in Homeless Shelters and Public Housing in New York City. Matern Child Health J. 2019. 23:572-577. doi:10.1007/s10995-018-2672-1. | Mediators/moderators; Intervention/exposure - KQ3
959 | Reis-Reilly, H, Fuller-Sankofa, N, Tibbs, C. Breastfeeding in the Community: Addressing Disparities Through Policy, Systems, and Environmental Changes Interventions. Journal of Human Lactation. 2018. 34:262-271. doi:10.1177/0890334418759055. | Outcome
960 | Remer, S, Russell, R, Furman, L. “All in Breastfeeding”: An Approach to Improving Breastfeeding Support at the Rainbow Center for Women and Children. Health Promot Pract. 2022. 15248399221096414. doi:10.1177/15248399221096414. | Outcome
961 | Rempel, LA, Rempel, JK, Moore, KCJ. Relationships between types of father breastfeeding support and breastfeeding outcomes. Matern Child Nutr. 2017. 13:e12337. doi:10.1111/mcn.12337. | Country
962 | Rempel, LA, Rempel, JK. The Breastfeeding Team: The Role of Involved Fathers in the Breastfeeding Family. Journal of Human Lactation. 2011. 27:115-121. doi:10.1177/0890334410390045. | Country
963 | Reno, R. A Pilot Study of a Culturally Grounded Breastfeeding Intervention for Pregnant, Low-Income African American Women. J Hum Lact. 2018. 34:478-484. doi:10.1177/0890334418775050. | Outcome
964 | Reno, R. Using group model building to develop a culturally grounded model of breastfeeding for low-income African American women in the USA. J Clin Nurs. 2018. 27:3363-3376. doi:10.1111/jocn.13791. | Intervention/exposure - KQ3; Outcome
965 | Requejo, J, Black, R. Strategies for reducing unnecessary in-hospital formula supplementation and increasing rates of exclusive breastfeeding. Journal of Pediatrics. 2014. 164:1256-1258. doi:10.1016/j.jpeds.2014.03.012. | Study design
966 | Rethy, JA, Gallo, S, Doig, AC, Brady, J, Goodfriend, D. Sociodemographic predictors of exclusive breast-feeding among low-income women attending a Special Supplemental Nutrition Program for Women, Infants, and Children (WIC) programme. Public Health Nutr. 2019. 22:1667-1674. doi:10.1017/s1368980019000119. | Intervention/exposure - KQ3; Independent variable - KQ2
967 | Reyes-Foster, BM, Carter, SK, Hinojosa, Melanie S. Human Milk Handling and Storage Practices Among Peer Milk-Sharing Mothers. Journal of Human Lactation. 2017. 33:173-180. doi:10.1177/0890334416678830. | Outcome
968 | Richards, E, Lanning, RK. Volunteer doulas’ experiences supporting cesarean births: A qualitative analysis for preliminary program evaluation. Midwifery. 2019. 77:117-122. doi:10.1016/j.midw.2019.07.001. | Study participants
969 | Richards, R, Merrill, RM, Baksh, L, McGarry, J. Maternal health behaviors and infant health outcomes among homeless mothers: U.S. Special Supplemental Nutrition Program for Women, Infants, and Children (WIC) 2000-2007. Prev Med. 2011. 52:87-94. doi:10.1016/j.ypmed.2010.10.010. | Mediators/moderators; Intervention/exposure - KQ3
970 | Richards, R, Merrill, RM, Baksh, L. Health behaviors and infant health outcomes in homeless pregnant women in the United States. Pediatrics. 2011. 128:438-46. doi:10.1542/peds.2010-3491. | Mediators/moderators; Intervention/exposure - KQ3
971 | Riley, B, Schoeny, M, Rogers, L, Asiodu, IV, Bigger, HR, Meier, PP, Patel, AL. Barriers to Human Milk Feeding at Discharge of Very Low-Birthweight Infants: Evaluation of Neighborhood Structural Factors. Breastfeed Med. 2016. 11:335-42. doi:10.1089/bfm.2015.0185. | Study Participants
972 | Rios, E. Promoting breastfeeding in the Hispanic community. Breastfeed Med. 2009. 4 Suppl 1:S69-70. doi:10.1089/bfm.2009.0065. | Outcome
973 | Rios-Ellis, B, Nguyen-Rodriguez, ST, Espinoza, L, Galvez, G, Garcia-Vega, M. Engaging Community With Promotores de Salud to Support Infant Nutrition and Breastfeeding Among Latinas Residing in Los Angeles County: Salud con Hyland’s. Health Care Women Int. 2015. 36:711-29. doi:10.1080/07399332.2014.900060. | Independent variable - KQ2; Comparator - KQ3
974 | Risica, PM, McCausland, K. Infant feeding decisions and behaviours among low-income smoke-exposed women: timing and change during pregnancy. Public Health Nutr. 2017. 20:2796-2805. doi:10.1017/s1368980017001690. | Mediators/moderators; Intervention/exposure - KQ3
975 | Risisky, D, Chan, RL, Zigmont, VA, Asghar, SM, DeGennaro, N. Examining Delivery Method and Infant Feeding Intentions between Women in Traditional and Non-Traditional Prenatal Care. Matern Child Health J. 2018. 22:274-282. doi:10.1007/s10995-017-2400-2. | Mediators/moderators; Study participants
976 | Ritchie-Ewing, G, Mitchell, AM, Christian, LM. Associations of Maternal Beliefs and Distress in Pregnancy and Postpartum With Breastfeeding Initiation and Early Cessation. Journal of Human Lactation. 2019. 35:49-58. doi:10.1177/0890334418767832. | Mediators/moderators; Intervention/exposure - KQ3
977 | Rivett, M. Can breastfeeding help to protect long-term maternal emotional health?. MIDIRS Midwifery Digest. 2017. 27:229-231. | Study design
978 | Rivett, M. Enablers of and barriers to the increased provision of human breast milk for preterm infants. MIDIRS Midwifery Digest. 2019. 29:225-230. | Study design
979 | Shah, R, Diaz, S, Arria, A, LaGasse, L, Derauf, C, Newman, E, Smith, L, Huestis, M, Haning, W, Strauss, A, Grotta, SD, Dansereau, L, Roberts, M, Neal, C, Lester, B. Prenatal Methamphetamine Exposure and Short-Term Maternal and Infant Medical Outcomes. American Journal of Perinatology. 2012. 29:391-400. | Intervention/exposure - KQ3; Independent variable - KQ2
980 | Robbins, JM, Thomas, D, Torcato, BR, Lisi, LM, Robbins, SW. Breastfeeding in an inner-city patient population. J Health Care Poor Underserved. 2011. 22:473-81. doi:10.1353/hpu.2011.0062. | Mediators/moderators; Intervention/exposure - KQ3
981 | Robinson, A, Lauckner, C, Davis, M, Hall, J, Anderson, AK. Facebook support for breastfeeding mothers: A comparison to offline support and associations with breastfeeding outcomes. Digit Health. 2019. 5:2055207619853397. doi:10.1177/2055207619853397. | Outcome
982 | Robinson, K. African American women’s infant feeding choices: Analyzing self-efficacy & narratives from a black feminist perspective. Marquette University; 2010. | Publication status
983 | Robinson, VC. Support for the hypothesis that sexual breast stimulation is an ancestral practice and a key to understanding women’s health. Med Hypotheses. 2015. 85:976-85. doi:10.1016/j.mehy.2015.09.002. | Study design
984 | Roess, AA, Jacquier, EF, Catellier, DJ, Carvalho, R, Lutes, AC, Anater, AS, Dietz, WH. Food Consumption Patterns of Infants and Toddlers: Findings from the Feeding Infants and Toddlers Study (FITS) 2016. J Nutr. 2018. 148:1525s-1535s. doi:10.1093/jn/nxy171. | Mediators/moderators; Intervention/exposure - KQ3
985 | Roess, AA, Robert, RC, Kuehn, D, Ume, N, Ericson, B, Woody, E, Vinjamuri, S, Thompson, P. Disparities in Breastfeeding Initiation Among African American and Black Immigrant WIC Recipients in the District of Columbia, 2007-2019. Am J Public Health. 2022. 112:671-674. doi:10.2105/ajph.2021.306652. | Mediators/moderators; Intervention/exposure - KQ3
986 | Roig, AO, Martínez, MR, García, JC, Hoyos, SP, Navidad, GL, Alvarez, JC, Pujalte Mdel, M, De León González, RG. Factors associated to breastfeeding cessation before 6 months. Rev Lat Am Enfermagem. 2010. 18:373-80. doi:10.1590/s0104-11692010000300012. | Country
987 | Rojjanasrirat, W, Sousa, VD. Perceptions of breastfeeding and planned return to work or school among low-income pregnant women in the USA. J Clin Nurs. 2010. 19:2014-22. doi:10.1111/j.1365-2702.2009.03152.x. | Study participants
988 | Rojjanasrirat, W, Wambach, KA, Sousa, VD, Gajewski, BJ. Psychometric evaluation of the Employer Support for Breastfeeding Questionnaire (ESBQ). J Hum Lact. 2010. 26:286-96. doi:10.1177/0890334410365066. | Outcome
989 | Rollins, BY, Francis, LA. Off the Charts: Identifying and Visualizing Body Mass Index Trajectories of Rural, Poor Youth. J Pediatr. 2021. 228:147-154.e2. doi:10.1016/j.jpeds.2020.09.007. | Outcome
990 | Rollins, L, Giddings, T, Henes, S, Culbreth, W, Coleman, AS, Smith, S, White, C, Nelson, T. Design and Implementation of a Nutrition and Breastfeeding Education Program for Black Expecting Mothers and Fathers. J Nutr Educ Behav. 2022. 54:794-803. doi:10.1016/j.jneb.2022.03.011. | Publication status; Other (Protocol)
991 | Romaine, A, Clark, RH, Davis, BR, Hendershot, K, Kite, V, Laughon, M, Updike, I, Miranda, ML, Meier, PP, Patel, AL, Smith, PB, Cotten, CM, Benjamin, DK, Jr, Greenberg, RG. Predictors of Prolonged Breast Milk Provision to Very Low Birth Weight Infants. J Pediatr. 2018. 202:23-30.e1. doi:10.1016/j.jpeds.2018.07.001. | Mediators/moderators; Intervention/exposure - KQ3
992 | Roncolato, W, McMahon, C, Grant, KA. Facilitators and regulators: antenatal maternal orientation and postnatal parenting practices. Journal of Reproductive & Infant Psychology. 2014. 32:214-229. doi:10.1080/02646838.2014.904962. | Country
993 | Roop, K, Brillhart, J. Supporting breastfeeding mothers: the Anthem Medicaid experience. Breastfeed Med. 2011. 6:293-4. doi:10.1089/bfm.2011.0061. | Study design
994 | Rosenbach, M, O’Neil, S, Cook, B, Trebino, L, Walker, DK. Characteristics, access, utilization, satisfaction, and outcomes of healthy start participants in eight sites. Matern Child Health J. 2010. 14:666-679. doi:10.1007/s10995-009-0474-1. | Mediators/moderators; Comparator - KQ3
995 | Rosen-Carole, C, Allen, K, Fagnano, M, Dozier, A, Halterman, J. Mothers’ Concerns for Personal Safety and Privacy While Breastfeeding: An Unexplored Phenomenon. Breastfeeding Medicine. 2018. 13:181-188. doi:10.1089/bfm.2017.0187. | Mediators/moderators; Intervention/exposure - KQ3
996 | Rosen-Carole, C, Waltermaurer, E, Goudreault, M, Larimer, A, Pokharel-Wood, M, Rajupet, S, Kouba, N. Assessing the Efficacy of a Breastfeeding-Friendly Quality Improvement Project in a Large Federally Qualified Health Center Network. Journal of Human Lactation. 2016. 32:489-497. doi:10.1177/0890334415610326. | Mediators/moderators; Study participants
997 | Rosenthal, A, Oliveira, SB, Madubuko, U, Tanuos, H, Schwab, J, Monteiro, IM. Effects of Immigration on Infant Feeding Practices in an Inner City, Low Socioeconomic Community. J Natl Med Assoc. 2019. 111:153-157. doi:10.1016/j.jnma.2018.07.006. | Mediators/moderators; Intervention/exposure - KQ3
998 | Ross, E, Woszidlo, A. Breastfeeding in the Workplace: Attitudes Toward Multiple Roles, Perceptions of Support, and Workplace Outcomes. Breastfeed Med. 2022. 17:38-45. doi:10.1089/bfm.2021.0119. | Intervention/exposure - KQ3; Independent variable - KQ2; Study participants
999 | Ross-Cowdery, M, Lewis, CA, Papic, M, Corbelli, J, Schwarz, EB. Counseling About the Maternal Health Benefits of Breastfeeding and Mothers’ Intentions to Breastfeed. Matern Child Health J. 2017. 21:234-241. doi:10.1007/s10995-016-2130-x. | Outcome
1000 | Rossin-Slater, M. WIC in Your Neighborhood: New Evidence on the Impacts of Geographic Access to Clinics. J Public Econ. 2013. 102:51-69. doi:10.1016/j.jpubeco.2013.03.009. | Intervention/exposure - KQ3; Independent variable - KQ2
1001 | Rossman, B, Engstrom, JL, Meier, PP, Vonderheid, SC, Norr, KF, Hill, PD. “They’ve Walked in My Shoes”: Mothers of Very Low Birth Weight Infants and Their Experiences With Breastfeeding Peer Counselors in the Neonatal Intensive Care Unit. Journal of Human Lactation. 2011. 27:14-24. doi:10.1177/0890334410390046. | Study participants
1002 | Rossman, B, Meier, PP, Janes, JE, Lawrence, C, Patel, AL. Human Milk Provision Experiences, Goals, and Outcomes for Teen Mothers with Low-Birth-Weight Infants in the Neonatal Intensive Care Unit. Breastfeed Med. 2017. 12:351-358. doi:10.1089/bfm.2017.0035. | Intervention/exposure - KQ3; Study participants
1003 | Rothschild, TJ, Fuks, A, Stein-Albert, M. Racial Disparities in Breastfeeding. Breastfeeding Medicine. 2015. 10:286-286. doi:10.1089/bfm.2015.0059. | Independent variable - KQ2; Study participants
1004 | Rouse, CL. Increasing Initiation and Exclusivity of Breastfeeding In the Hospitalized Postpartum Dyad. Walden University; 2015. | Publication status
1005 | Rowe-Finkbeiner, K, Martin, R, Abrams, B, Zuccaro, A, Dardari, Y. Why Paid Family and Medical Leave Matters for the Future of America’s Families, Businesses and Economy. Matern Child Health J. 2016. 20:8-12. doi:10.1007/s10995-016-2186-7. | Study design
1006 | Rozga, MR, Benton, PA, Kerver, JM, Olson, BH. An Integrated Model of Breastfeeding Peer Counseling Support is Feasible and Associated with Improved Exclusive Breastfeeding. Matern Child Health J. 2016. 20:2589-2598. doi:10.1007/s10995-016-2086-x. | Mediators/moderators; Study participants
1007 | Rozga, MR, Kerver, JM, Olson, BH. Impact of peer counselling breast-feeding support programme protocols on any and exclusive breast-feeding discontinuation in low-income women. Public Health Nutrition. 2015. 18:453-463. doi:10.1017/s1368980014000603. | Mediators/moderators; Study participants
1008 | Rozga, MR, Kerver, JM, Olson, BH. Prioritization of resources for participants in a peer counseling breastfeeding support program. J Hum Lact. 2015. 31:111-9. doi:10.1177/0890334414554420. | Mediators/moderators; Study participants
1009 | Rozga, MR, Kerver, JM, Olson, BH. Self-reported reasons for breastfeeding cessation among low-income women enrolled in a peer counseling breastfeeding support program. J Hum Lact. 2015. 31:129-37; quiz 189-90. doi:10.1177/0890334414548070. | Mediators/moderators; Intervention/exposure - KQ3; Study participants
1010 | Rubin, R. Possible Racial Disparities in NICU Breast Milk Use. Jama. 2018. 319:334. doi:10.1001/jama.2017.20797. | Study design; Othe (Summary of peer reviewed article)
1011 | Rubin, R. Despite Potential Health Benefits of Maternity Leave, US Lags Behind Other Industrialized Countries. JAMA: Journal of the American Medical Association. 2016. 315:643-645. doi:10.1001/jama.2015.18609. | Study design
1012 | Ruffin, SD, Renaud, M. Prenatal Education, Significant Other Support and Demographic Determinants of Breastfeeding within a Rural Community. Online Journal of Rural Nursing & Health Care. 2015. 15:132-151. doi:10.14574/ojrnhc.v15i2.372. | Mediators/moderators; Study participants
1013 | Russell, CG, Taki, S, Azadi, L, Campbell, KJ, Laws, R, Elliott, R, Denney-Wilson, E. A qualitative study of the infant feeding beliefs and behaviours of mothers with low educational attainment. BMC Pediatr. 2016. 16:69. doi:10.1186/s12887-016-0601-2. | Country
1014 | Sabharwal, V, Bartolome, R, Hassan, SA, Levesque, BM, Camelo, IY, Wachman, EM, Figueira, M, Yarrington, CD, Cooper, ER, Barnett, ED, Parker, MG. Mother–Infant Dyads with COVID-19 at an Urban, Safety-Net Hospital: Clinical Manifestations and Birth Outcomes. American Journal of Perinatology. 2021. 38:741-746. doi:10.1055/s-0041-1726429. | Mediators/moderators; Intervention/exposure - KQ3
1015 | Sadacharan, R, Grossman, X, Matlak, S, Merewood, A. Hospital Discharge Bags and Breastfeeding at 6 Months: Data from the Infant Feeding Practices Study II. Journal of Human Lactation. 2014. 30:73-79. doi:10.1177/0890334413513653. | Mediators/moderators; Intervention/exposure - KQ3
1016 | Sağlam, NÖ, Bülbül, L, Kazancı, SY, Hatipoğlu, SS. Factors Affecting Breastfeeding and Complementary Feeding Choices for Children Aged 24 to 48 Months. Sisli Etfal Hastan Tip Bul. 2019. 53:165-171. doi:10.14744/semb.2018.91328. | Country
1017 | Salganicoff, A. The Importance of Strengthening Workplace and Health Policies to Support Breastfeeding. Breastfeed Med. 2018. 13:532-534. doi:10.1089/bfm.2018.0122. | Study design
1018 | Salm Ward, TC, Ngui, EM. Factors associated with bed-sharing for African American and White mothers in Wisconsin. Matern Child Health J. 2015. 19:720-32. doi:10.1007/s10995-014-1545-5. | Outcome
1019 | Santacruz-Salas, E, Segura-Fragoso, A, Cobo-Cuenca, AI, Carmona-Torres, JM, Pozuelo-Carrascosa, DP, Laredo-Aguilera, JA. Factors Associated with the Abandonment of Exclusive Breastfeeding before Three Months. Children (Basel). 2020. 7:298. doi:10.3390/children7120298. | Country
1020 | Sattari, M, Levine, DM, Mramba, LK, Pina, M, Raukas, R, Rouw, E, Serwint, JR. Physician Mothers and Breastfeeding: A Cross-Sectional Survey. Breastfeed Med. 2020. 15:312-320. doi:10.1089/bfm.2019.0193. | Independent variable - KQ2; Study participants
1021 | Sattari, M, Serwint, JR, Neal, D, Chen, S, Levine, DM. Work-place predictors of duration of breastfeeding among female physicians. J Pediatr. 2013. 163:1612-7. doi:10.1016/j.jpeds.2013.07.026. | Mediators/moderators; Study participants
1022 | Sattari, M, Serwint, JR, Shuster, JJ, Levine, DM. Infant-Feeding Intentions and Practices of Internal Medicine Physicians. Breastfeed Med. 2016. 11:173-9. doi:10.1089/bfm.2015.0151. | Independent variable - KQ2; Study participants
1023 | Sauder, KA, Bekelman, TA, Harrall, KK, Glueck, DH, Dabelea, D. Gestational diabetes exposure and adiposity outcomes in childhood and adolescence: An analysis of effect modification by breastfeeding, diet quality, and physical activity in the EPOCH study. Pediatric Obesity. 2019. 14:N.PAG-N.PAG. doi:10.1111/ijpo.12562. | Outcome
1024 | Savage, JH, Lee-Sarwar, KA, Sordillo, JE, Lange, NE, Zhou, Y, O’Connor, GT, Sandel, M, Bacharier, LB, Zeiger, R, Sodergren, E, Weinstock, GM, Gold, DR, Weiss, ST, Litonjua, AA. Diet during Pregnancy and Infancy and the Infant Intestinal Microbiome. J Pediatr. 2018. 203:47-54.e4. doi:10.1016/j.jpeds.2018.07.066. | Outcome
1025 | Schafer, EJ, Campo, S, Colaizy, TT, Mulder, PJ, Breheny, P, Ashida, S. First-time mothers’ breast-feeding maintenance: role of experiences and changes in maternal perceptions. Public Health Nutrition. 2017. 20:3099-3108. doi:10.1017/s136898001700221x. | Mediators/moderators; Intervention/exposure - KQ3
1026 | Schafer, EJ, Livingston, TA, Roig-Romero, RM, Wachira, M, Louis-Jacques, AF, Marhefka, SL. “Breast Is Best, But…” According to Childcare Administrators, Not Best for the Childcare Environment. Breastfeed Med. 2021. 16:21-28. doi:10.1089/bfm.2020.0078. | Outcome
1027 | Schafer, EJ, Williams, NA, Digney, S, Hare, ME, Ashida, S. Social Contexts of Infant Feeding and Infant Feeding Decisions. J Hum Lact. 2016. 32:132-40. doi:10.1177/0890334415592850. | Mediators/moderators; Intervention/exposure - KQ3
1028 | Scharfe, E. Maternal attachment representations and initiation and duration of breastfeeding. J Hum Lact. 2012. 28:218-25. doi:10.1177/0890334411429111. | Mediators/moderators; Intervention/exposure - KQ3
1029 | Scheiber, FA, Segre, LS, O’Hara, MW, Taylor, D, Brock, RL. Maternal depression and breastfeeding in home visitation. Child Youth Serv Rev. 2020. 119:105490. doi:10.1016/j.childyouth.2020.105490. | Mediators/moderators; Comparator - KQ3
1030 | Scheid, CR, Paulson, JL, Miller-Graff, LE. Feelings and feedings: Psychopathology and breastfeeding attitudes in women with a history of intimate partner violence. Psychol Trauma. 2021. 13:394-402. doi:10.1037/tra0000984. | Intervention/exposure - KQ3; Independent variable - KQ2; Study participants
1031 | Schindler-Ruwisch, J, Roess, A, Robert, RC, Kuehn, D, Woody, E, Vinjamuri, S, Thompson, P. Smoking and Race Associated with Decreased Breastfeeding Initiation and Duration Among a Low Income Population. Breastfeed Med. 2021. 16:878-885. doi:10.1089/bfm.2021.0136. | Mediators/moderators; Intervention/exposure - KQ3
1032 | Schliep, KC, Denhalter, D, Gren, LH, Panushka, KA, Singh, TP, Varner, MW. Factors in the Hospital Experience Associated with Postpartum Breastfeeding Success. Breastfeed Med. 2019. 14:334-341. doi:10.1089/bfm.2018.0039. | Mediators/moderators; Study participants
1033 | Schoenfelder, SL, Wych, S, Willows, CA, Harrington, J, Christoffel, KK, Becker, AB. Engaging Chicago hospitals in the baby-friendly hospital initiative. Matern Child Health J. 2013. 17:1712-7. doi:10.1007/s10995-012-1144-2. | Outcome
1034 | Schroeder, N, Rushovich, B, Bartlett, E, Sharma, S, Gittelsohn, J, Caballero, B. Early Obesity Prevention: A Randomized Trial of a Practice-Based Intervention in 0-24-Month Infants. J Obes. 2015. 2015:795859. doi:10.1155/2015/795859. | Mediators/moderators; Study participants
1035 | Schulze, PA, Zhao, B, Young, CE. Beliefs about infant feeding in China and the United States: implications for breastfeeding promotion. Ecol Food Nutr. 2009. 48:345-68. doi:10.1080/03670240903170475. | Mediators/moderators; Intervention/exposure - KQ3; Comparator - KQ2; Study participants
1036 | Schwabl, K. Breastfeeding Problems and Interventions for Underserved Populations. Clinical Lactation. 2017. 8:28-33. doi:10.1891/2158-0782.8.1.28. | Outcome
1037 | Schwartz, R, Ellings, A, Baisden, A, Goldhammer, CJ, Lamson, E, Johnson, D. Washington ‘Steps’ Up: A 10-Step Quality Improvement Initiative to Optimize Breastfeeding Support in Community Health Centers. J Hum Lact. 2015. 31:651-9. doi:10.1177/0890334415591147. | Outcome
1038 | Schwarzenberg, SJ, Georgieff, MK. Advocacy for Improving Nutrition in the First 1000 Days to Support Childhood Development and Adult Health. Pediatrics. 2018. 141: e20173716. doi:10.1542/peds.2017-3716. | Study design
1039 | Schwichtenberg, AJ, Poehlmann, J. A transactional model of sleep-wake regulation in infants born preterm or low birthweight. J Pediatr Psychol. 2009. 34:837-49. doi:10.1093/jpepsy/jsn132. | Mediators/moderators; Intervention/exposure - KQ3
1040 | Schy, D, Leonardi, N, Kozmic, SE, Wiesbrock, J, Sulo, S. Pumping Practices and Characteristics of Mothers With Preterm Babies Going to the Neonatal Intensive Care Unit. Clinical Lactation. 2017. 8:66-73. doi:10.1891/2158-0782.8.2.66. | Intervention/exposure - KQ3; Independent variable - KQ2; Study participants
1041 | Scott, VC, Taylor, YJ, Basquin, C, Venkitsubramanian, K. Impact of Key Workplace Breastfeeding Support Characteristics on Job Satisfaction, Breastfeeding Duration, and Exclusive Breastfeeding Among Health Care Employees. Breastfeed Med. 2019. 14:416-423. doi:10.1089/bfm.2018.0202. | Mediators/moderators; Intervention/exposure - KQ3
1042 | Seabolt, L. Nurses for breastfeeding: policy alert. S C Nurse (1994). 2012. 19:11. | Study design
1043 | Seal, N, Broome, ME. Prepregnancy Body Mass Index and Feeding Practices in Relation to Infants’ Growth. J Nurse Pract. 2013. 9:270-6. doi:10.1016/j.nurpra.2013.01.017. | Outcome
1044 | Sedler, J, Khaki, IS, Phillipi, CA, Dukhovny, D, DeVane, K, Gievers, L. Quality Improvement Analyses Revealed a Hidden Shift Following a Retrospective Study on Breastfeeding Rates. Pediatr Qual Saf. 2020. 5:e347. doi:10.1097/pq9.0000000000000347. | Mediators/moderators; Study participants
1045 | See, H, Smith-Gagen, J, Hollen, Robin, White, LL, Christiansen, EJ. Pragmatic Effectiveness of the Loving Support Peer Counseling Program to Increase Breastfeeding Duration Among Nevada WIC Participants. Clinical Lactation. 2018. 9:72-77. doi:10.1891/2158-0782.9.2.72. | Mediators/moderators; Study participants
1046 | Seipel, MMO, Shafer, K. The Effect of Prenatal and Postnatal Care on Childhood Obesity. Social Work. 2013. 58:241-252. doi:10.1093/sw/swt025. | Outcome
1047 | Sekhobo, JP. Estimation of WIC effects in multilevel, cross-sector obesity prevention interventions. Obesity (19307381). 2017. 25:1157-1158. doi:10.1002/oby.21891. | Study design
1048 | Sen, S, Rifas-Shiman, SL, Shivappa, N, Wirth, MD, Hebert, JR, Gold, DR, Gillman, MW, Oken, E. Dietary Inflammatory Potential during Pregnancy Is Associated with Lower Fetal Growth and Breastfeeding Failure: Results from Project Viva. Journal of Clinical Chiropractic Pediatrics. 2017. 16:1381-1381. doi:10.3945/jn.115.225581. | Intervention/exposure - KQ3; Independent variable - KQ2
1049 | Senol, DK, Yurdakul, M, Ozkan, SA. The effect of maternal fatigue on breastfeeding. Nigerian Journal of Clinical Practice. 2019. 22:1662-1668. doi:10.4103/njcp.njcp_576_18. | Country
1050 | Seshadri, N, Kim, LY, McGrath-Morrow, SA, Collaco, JM. Human Milk Cessation in the NICU in Infants with Bronchopulmonary Dysplasia. Am J Perinatol. 2021. doi:10.1055/a-1692-0796. | Mediators/moderators; Study participants
1051 | Setiawati, N, Setyowati, Budiati, T. SETIA Health Education Set Enhances Knowledge, Attitude, and Parenting Self-Efficacy Score in Postpartum Adolescent Mothers. Comprehensive Child & Adolescent Nursing. 2017. 40:114-127. doi:10.1080/24694193.2017.1386979. | Country
1052 | Shah, PV, Tong, S, Hwang, SS, Bourque, SL. Racial/Ethnic Differences in Prenatal and Postnatal Counseling About Maternal and Infant Health-Promoting Practices Among Teen Mothers. J Pediatr Adolesc Gynecol. 2021. 34:40-46. doi:10.1016/j.jpag.2020.10.002. | Outcome
1053 | Shamberger, RJ. Autism rates associated with nutrition and the WIC program. J Am Coll Nutr. 2011. 30:348-53. doi:10.1080/07315724.2011.10719978. | Independent variable - KQ2; Outcome
1054 | Sharma, SV, Chuang, RJ, Byrd-Williams, C, Danho, M, Upadhyaya, M, Berens, P, Hoelscher, DM. Pilot evaluation of HEAL - A natural experiment to promote obesity prevention behaviors among low-income pregnant women. Prev Med Rep. 2018. 10:254-262. doi:10.1016/j.pmedr.2018.04.005. | Outcome
1055 | Shaughnessy, AF. Provided Infant Carriers Increase the Rate of Sustained Breastfeeding. American Family Physician. 2022. 105:93-94. | Study design; Publication status
1056 | Shim, JE, Kim, J, Heiniger, JB. Breastfeeding duration in relation to child care arrangement and participation in the special supplemental nutrition program for women, infants, and children. J Hum Lact. 2012. 28:28-35. doi:10.1177/0890334411424728. | Independent variable - KQ2; Study participants
1057 | Shin, CN, Reifsnider, E, McClain, D, Jeong, M, McCormick, DP, Moramarco, M. Acculturation, Cultural Values, and Breastfeeding in Overweight or Obese, Low-Income, Hispanic Women at 1 Month Postpartum. J Hum Lact. 2018. 34:358-364. doi:10.1177/0890334417753942. | Intervention/exposure - KQ3; Comparator - KQ2
1058 | Shinn, LM, Tangney, CC, Busche, C, Sharp, CM, Mullen, MC. Demographic Correlates of Infant Feeding Practices and Growth Performance in the First Year of Life. Int J Pediatr. 2018. 2018:6569204. doi:10.1155/2018/6569204. | Mediators/moderators; Intervention/exposure - KQ3; Outcome
1059 | Shipp, GM, Weatherspoon, LJ, Comstock, SS, Norman, GS, Alexander, GL, Gardiner, JC, Kerver, JM. Breastfeeding Self-Efficacy as a Predictor of Breastfeeding Intensity Among African American Women in the Mama Bear Feasibility Trial. Breastfeed Med. 2022. 17:453-458. doi:10.1089/bfm.2021.0301. | Outcome
1060 | Shlafer, RJ, Davis, L, Hindt, LA, Goshin, LS, Gerrity, E. Intention and Initiation of Breastfeeding Among Women Who Are Incarcerated. Nursing for Women’s Health. 2018. 22:64-77. doi:10.1016/j.nwh.2017.12.004. | Intervention/exposure - KQ3; Study participants
1061 | Shore, JH, Waugh, M, Calderone, J, Donahue, A, Rodriguez, J, Peters, D, Thomas, M, Giese, A. Evaluation of Telepsychiatry-Enabled Perinatal Integrated Care. Psychiatric Services. 2020. 71:427-432. doi:10.1176/appi.ps.201900143. | Independent variable - KQ2; Comparator - KQ3
1062 | Shumbusho, DI, Kucera, CW, Keyser, EA. Maternity Leave Length Impact on Breastfeeding and Postpartum Depression. Mil Med. 2020. 185:1937-1940. doi:10.1093/milmed/usaa137. | Independent variable - KQ2; Study participants
1063 | Shviraga, B. Critical enthnography of Mexican primiparas regarding exclusive breastfeeding. Communicating Nursing Research. 2012. 45:358-358. | Publication status
1064 | Shviraga, BA. A critical ethnographic study of the cultural values, beliefs, and practices of recently immigrated Mexican primiparas regarding infant feeding with a focus on exclusive breastfeeding. University of Colorado Denver; 2011. | Publication status
1065 | Siggia, G, Rosenberg, S. Does Breastfeeding Education of Nurses Increase Exclusive Breastfeeding Rates in a Large Academic Medical Institution?. JOGNN: Journal of Obstetric, Gynecologic & Neonatal Nursing. 2014. 43:S38-S38. doi:10.1111/1552-6909.12416. | Publication status
1066 | Sigman-Grant, M. WIC and Breastfeeding. Journal of Nutrition Education & Behavior. 2017. 49:S137-S138. doi:10.1016/j.jneb.2017.05.342. | Study design; Publication status
1067 | Silbert-Flagg, JA, Busch, D, Bataille, JA. Mothers’ Perceptions of the Influence of a Breastfeeding Support Group in Achieving Their Breastfeeding Goals. Clinical Lactation. 2020. 11:74-83. doi:10.1891/CLINLACT-D-19-00019. | Study participants
1068 | Silva, CS, Lima, MC, Sequeira-de-Andrade, LAS, Oliveira, JS, Monteiro, JS, Lima, NMS, Santos, Rmab, Lira, PIC. Association between postpartum depression and the practice of exclusive breastfeeding in the first three months of life. J Pediatr (Rio J). 2017. 93:356-364. doi:10.1016/j.jped.2016.08.005. | Country
1069 | Simonelli, MC, Velicer, WF. Cluster subtypes appropriate for preventing postpartum smoking relapse. Addict Behav. 2012. 37:280-6. doi:10.1016/j.addbeh.2011.11.001. | Outcome
1070 | Simonetti, V, Palma, E, Giglio, A, Mohn, A, Cicolini, G. A structured telephonic counselling to promote the exclusive breastfeeding of healthy babies aged zero to six months: A pilot study. International Journal of Nursing Practice (John Wiley & Sons, Inc.). 2012. 18:289-294. doi:10.1111/j.1440-172X.2012.02040.x. | Country
1071 | Singleton, U. Creating a culture of breastfeeding to reduce disparities. J Hum Lact. 2015. 31:17-20. doi:10.1177/0890334414556538. | Study design
1072 | Sinigaglia, OE, Ríos, EM, Campos, M, Díaz, B, Palacios, C. Breastfeeding practices, timing of introduction of complementary beverages and foods and weight status in infants and toddlers participants of a WIC clinic in Puerto Rico. Springerplus. 2016. 5:1437. doi:10.1186/s40064-016-3154-9. | Intervention/exposure - KQ3; Comparator - KQ2
1073 | Sipsma, HL, Divney, AA, Magriples, U, Hansen, N, Gordon, D, Kershaw, T. Breastfeeding Intentions Among Pregnant Adolescents and Young Adults and Their Partners. Breastfeeding Medicine. 2013. 8:374-380. doi:10.1089/bfm.2012.0111. | Outcome
1074 | Sipsma, HL, Jones, K, Nickel, NC. Hospital practices to promote breastfeeding: The effect of maternal age. Birth-Issues in Perinatal Care. 2017. 44:272-280. doi:10.1111/birt.12284. | Mediators/moderators; Study participants
1075 | Sipsma, HL, Rabinowitz, MR, Young, D, Phillipi, C, Larson, IA, Kair, LR. Exposure to Hospital Breastfeeding Support by Maternal Race and Ethnicity: A Pilot Study. J Midwifery Womens Health. 2019. 64:743-748. doi:10.1111/jmwh.13048. | Outcome
1076 | Sisk, PM, Lovelady, CA, Dillard, RG, Gruber, KJ, O’Shea, TM. Maternal and infant characteristics associated with human milk feeding in very low birth weight infants. J Hum Lact. 2009. 25:412-9. doi:10.1177/0890334409340776. | Mediators/moderators; Intervention/exposure - KQ3
1077 | Škledar, MT, Milošević, M. Breastfeeding and time of complementary food introduction as predictors of obesity in children. Cent Eur J Public Health. 2015. 23:26-31. doi:10.21101/cejph.a3956. | Country
1078 | Sloand, E, Budhathoki, C, Junn, J, Vo, D, Lowe, V, Pennington, A. Breastfeeding among Latino Families in an Urban Pediatric Office Setting. Nurs Res Pract. 2016. 2016:9278401. doi:10.1155/2016/9278401. | Mediators/moderators; Intervention/exposure - KQ3
1079 | Smith, JP. A warrior for women’s and children’s rights to food and breastfeeding. Essence: Newsletter of the Australian Breastfeeding Association. 2022. 58:14-15. | Study design
1080 | Smith, LA, Geller, NL, Kellams, AL, Colson, ER, Rybin, DV, Heeren, T, Corwin, MJ. Infant Sleep Location and Breastfeeding Practices in the United States, 2011-2014. Acad Pediatr. 2016. 16:540-9. doi:10.1016/j.acap.2016.01.021. | Mediators/moderators; Study design; Study participants
1081 | Snyder, K, Hansen, K, Brown, S, Portratz, A, White, K, Dinkel, D. Workplace Breastfeeding Support Varies by Employment Type: The Service Workplace Disadvantage. Breastfeed Med. 2018. 13:23-27. doi:10.1089/bfm.2017.0074. | Intervention/exposure - KQ3; Independent variable - KQ2; Study participants
1082 | Snyder, K, Hulse, E, Dingman, H, Cantrell, A, Hanson, C, Dinkel, D. Examining supports and barriers to breastfeeding through a socio-ecological lens: a qualitative study. Int Breastfeed J. 2021. 16:52. doi:10.1186/s13006-021-00401-4. | Intervention/exposure - KQ3; Independent variable - KQ2
1083 | Snyder, K, Worlton, G. Social Support During COVID-19: Perspectives of Breastfeeding Mothers. Breastfeed Med. 2021. 16:39-45. doi:10.1089/bfm.2020.0200. | Independent variable - KQ2; Study participants
1084 | Snyder, Kailey, Peterson, Julie, Bargstadt-Wilson, Kari. “No One Told Me About This Part”: What Breastfeeding Women Want and Need to Support Their Physical Health. Journal of Women’s Health Physical Therapy. 2021. 45:51-56. doi:10.1097/JWH.0000000000000195. | Intervention/exposure - KQ3; Independent variable - KQ2
1085 | Sonchak, L. The impact of WIC on breastfeeding initiation and gestational weight gain: Case study of South Carolina Medicaid mothers. Children and Youth Services Review. 2017. 79:115-125. doi:10.1016/j.childyouth.2017.05.024. | Comparator - KQ2; Study participants
1086 | Soni, S, Gupta, A, Jacobs, AJ. Exclusive breastfeeding rates in a multiethnic population at a community hospital. J Reprod Med. 2011. 56:195-8. | Mediators/moderators; Intervention/exposure - KQ3
1087 | Sorkio, S, Cuthbertson, D, Bärlund, S, Reunanen, A, Nucci, AM, Berseth, CL, Koski, K, Ormisson, A, Savilahti, E, Uusitalo, U, Ludvigsson, J, Becker, DJ, Dupré, J, Krischer, JP, Knip, M, Akerblom, HK, Virtanen, SM. Breastfeeding patterns of mothers with type 1 diabetes: results from an infant feeding trial. Diabetes Metab Res Rev. 2010. 26:206-11. doi:10.1002/dmrr.1074. | Intervention/exposure - KQ3; Country; Independent variable - KQ2
1088 | Soti-Ulberg, C, Hromi-Fiedler, A, Hawley, NL, Naseri, T, Manuele-Magele, A, Ah-Ching, J, Pérez-Escamilla, R. Scaling up breastfeeding policy and programs in Samoa: application of the Becoming Breastfeeding Friendly initiative. Int Breastfeed J. 2020. 15:1. doi:10.1186/s13006-019-0245-6. | Country
1089 | Souza, MHN, Souza, IEO, Tocantins, FR. The use of social network methodological framework in nursing care to breastfeeding women. Revista Latino-Americana de Enfermagem (RLAE). 2009. 17:354-360. doi:10.1590/S0104-11692009000300012. | Country
1090 | Spatz, DL. Breastfeeding. The Need to Improve Human Milk Rates for Vulnerable Infants. MCN: The American Journal of Maternal Child Nursing. 2019. 44:360-360. doi:10.1097/nmc.0000000000000574. | Study design
1091 | Spatz, DL. Changing institutional culture to value human milk. Advances in Neonatal Care (Lippincott Williams & Wilkins). 2014. 14:234-235. doi:10.1097/ANC.0000000000000128. | Study design
1092 | Spatz, DL. Disparities in Breastfeeding and Use of Pasteurized Donor Human Milk. MCN: The American Journal of Maternal Child Nursing. 2020. 45:374-374. doi:10.1097/NMC.0000000000000668. | Study design
1093 | Spatz, DL, Evans, A, Froh, E. Creation of a Regional Human Milk Assembly: A Model to Influence Practice and Policy Change in the NICU. Adv Neonatal Care. 2017. 17:417-423. doi:10.1097/anc.0000000000000393. | Outcome
1094 | Spatz, DL, Froh, EB, Flynn-Roth, R, Barton, S. Improving practice at the point of care through the optimization of the breastfeeding resource nurse model. J Obstet Gynecol Neonatal Nurs. 2015. 44:412-8. doi:10.1111/1552-6909.12570. | Study participants
1095 | Spatz, DL, Kim, GS, Froh, EB. Outcomes of a hospital-based employee lactation program. Breastfeed Med. 2014. 9:510-4. doi:10.1089/bfm.2014.0058. | Mediators/moderators; Study participants
1096 | Spatz, DL. Using World Breastfeeding Week to Transform Institutional Culture. MCN Am J Matern Child Nurs. 2020. 45:126. doi:10.1097/nmc.0000000000000608. | Outcome
1097 | Specker, BL, Minett, M, Beare, T, Poppinga, N, Carpenter, M, Munger, J, Strasser, K, Ahrendt, L. Safe Sleep Behaviors Among South Dakota Mothers and the Role of the Healthcare Provider. S D Med. 2020. 73:152-162. | Mediators/moderators; Intervention/exposure - KQ3; Study participants
1098 | Spinelli, MG, Endicott, J, Goetz, RR. Increased breastfeeding rates in black women after a treatment intervention. Breastfeed Med. 2013. 8:479-84. doi:10.1089/bfm.2013.0051. | Mediators/moderators; Study participants
1099 | Srinivas, GL, Benson, M, Worley, S, Schulte, E. A clinic-based breastfeeding peer counselor intervention in an urban, low-income population: interaction with breastfeeding attitude. J Hum Lact. 2015. 31:120-8. doi:10.1177/0890334414548860. | Mediators/moderators; Study participants
1100 | St Fleur, R, McKeever, J. The role of the nurse-physician leadership dyad in implementing the Baby-Friendly Hospital Initiative. Nurs Womens Health. 2014. 18:231-5. doi:10.1111/1751-486x.12124. | Outcome
1101 | St Fleur, R, Petrova, A. Knowledge and perception of breastfeeding practices in Hispanic mothers in association with their preferred language for communication. Breastfeed Med. 2014. 9:261-5. doi:10.1089/bfm.2013.0145. | Mediators/moderators; Intervention/exposure - KQ3
1102 | Stack, SW, Jagsi, R, Biermann, JS, Lundberg, GP, Law, KL, Milne, CK, Williams, SG, Burton, TC, Larison, CL, Best, JA. Maternity Leave in Residency: A Multicenter Study of Determinants and Wellness Outcomes. Acad Med. 2019. 94:1738-1745. doi:10.1097/acm.0000000000002780. | Study participants
1103 | Stack, SW, McKinney, CM, Spiekerman, C, Best, JA. Childbearing and maternity leave in residency: determinants and well-being outcomes. Postgrad Med J. 2018. 94:694-699. doi:10.1136/postgradmedj-2018-135960. | Mediators/moderators; Study participants
1104 | Stafford, JD, Goggins, ER, Lathrop, E, Haddad, LB. Health Literacy and Associated Outcomes in the Postpartum Period at Grady Memorial Hospital. Matern Child Health J. 2021. 25:599-605. doi:10.1007/s10995-020-03030-1. | Intervention/exposure - KQ3; Independent variable - KQ2
1105 | Stallaert, L. The Nurse’s Role in Acknowledging Women’s Emotions of Unmet Breastfeeding Expectations. Nursing for Women’s Health. 2020. 24:319-324. doi:10.1016/j.nwh.2020.07.002. | Study design
1106 | Stallings, VA. Feeding Infants and Toddlers Study (FITS) 2016: Findings and Thoughts on the Third Data Cycle. Journal of Nutrition. 2018. 148:1513S-1515S. doi:10.1093/jn/nxy158. | Mediators/moderators; Intervention/exposure - KQ3
1107 | Stampfel, C. National-level leadership in support of breastfeeding. Breastfeeding Medicine. 2013. 8:442-444. doi:10.1089/bfm.2013.0088. | Outcome
1108 | Stapleton, S, Wright, J, Jolles, DR. Improving the Experience of Care: Results of the American Association of Birth Centers Strong Start Client Experience of Care Registry Pilot Program, 2015-2016. J Perinat Neonatal Nurs. 2020. 34:27-37. doi:10.1097/jpn.0000000000000454. | Mediators/moderators; Study participants
1109 | Stark, GE. Catholic social teaching and America’s suboptimal breastfeeding rate: Where faith and policy should meet to combat injustice. Linacre Q. 2017. 84:356-366. doi:10.1080/00243639.2017.1384268. | Study design
1110 | Stearns, CA. Cautionary Tales About Extended Breastfeeding and Weaning. Health Care for Women International. 2011. 32:538-554. doi:10.1080/07399332.2010.540051. | Study participants
1111 | Stewart-Glenn, J. “I’ve Accomplished Something Here” The Lived Experience of Employed Breastfeeding Mothers: A Phenomenological Analysis. Journal of Pediatric Healthcare. 2014. 28:e52-3. doi:10.1016/j.pedhc.2014.08.008. | Publication status
1112 | St-Germain, AAF, Kirby, RSS, Urquia, MLL. Reproductive health among married and unmarried mothers aged less than 18, 18-19, and 20-24 years in the United States, 2014-2019: A population-based cross-sectional study. Plos Medicine. 2022. 19:20. doi:10.1371/journal.pmed.1003929. | Intervention/exposure - KQ3; Independent variable - KQ2
1113 | Stokowski, LA. Encouraging African American Mothers To Breastfeed. Advances in Neonatal Care. 2014. 14:237-237. | Study design
1114 | Stowe, G, Schleif, EP, Perry, JL, Briley, PM. Impact of Insurance Status on Initiation of Breast Milk Feeding Among Infants With CL ± P. Cleft Palate Craniofac J. 2022. 10556656221087553. doi:10.1177/10556656221087553. | Mediators/moderators; Intervention/exposure - KQ3
1115 | Strauch, J, Rohrer, JE, Refaat, A. Increased hospital documentation requirements may not increase breastfeeding among first-time mothers. J Eval Clin Pract. 2016. 22:194-9. doi:10.1111/jep.12453. | Mediators/moderators; Study participants
1116 | Street, DJ. Infant feeding attitudes, feeding method choice, and breastfeeding initiation among African American and Caucasian women. University of North Carolina at Greensboro; 2011. | Publication status
1117 | Street, DJ, Lewallen, LP. The influence of culture on breast-feeding decisions by African American and white women. J Perinat Neonatal Nurs. 2013. 27:43-51. doi:10.1097/JPN.0b013e31827e57e7. | Outcome; Study participants
1118 | Stucky, MG, Jolles, D, Stucky, CH. Right care: Improving timeliness and promoting preventive health in a lower socioeconomic reproductive health clinic. Nurs Forum. 2020. 55:407-415. doi:10.1111/nuf.12445. | Outcome
1119 | Stuebe, AM, Bonuck, K. What predicts intent to breastfeed exclusively? Breastfeeding knowledge, attitudes, and beliefs in a diverse urban population. Breastfeed Med. 2011. 6:413-20. doi:10.1089/bfm.2010.0088. | Outcome
1120 | Stuebe, AM, Horton, BJ, Chetwynd, E, Watkins, S, Grewen, K, Meltzer-Brody, S. Prevalence and risk factors for early, undesired weaning attributed to lactation dysfunction. J Womens Health (Larchmt). 2014. 23:404-12. doi:10.1089/jwh.2013.4506. | Mediators/moderators; Intervention/exposure - KQ3
1121 | Stuebe, AM, Meltzer-Brody, S, Propper, C, Pearson, B, Beiler, P, Elam, M, Walker, C, Mills-Koonce, R, Grewen, K. The Mood, Mother, and Infant Study: Associations Between Maternal Mood in Pregnancy and Breastfeeding Outcome. Breastfeed Med. 2019. 14:551-559. doi:10.1089/bfm.2019.0079. | Mediators/moderators; Intervention/exposure - KQ3
1122 | Sturtevant, C, Huebner, C, Waite, W. An Evaluation of On-Campus Lactation Spaces for Student-Parents. J Hum Lact. 2021. 37:173-182. doi:10.1177/0890334419888715. | Outcome; Study participants
1123 | Suberi, M, Morag, I, Strauss, T, Geva, R. Feeding Imprinting: The Extreme Test Case of Premature Infants Born With Very Low Birth Weight. Child Dev. 2018. 89:1553-1566. doi:10.1111/cdev.12923. | Country
1124 | Sullivan, K, Belfort, MB, Melvin, P, Angelidou, A, Peaceman, A, Shui, JE, Vaidya, R, Singh, R, Bartolome, R, Patrizi, S, Chaudhary, N, Goldfarb, IT, Culic, I, Yanni, D, Gupta, M, Hudak, M, Parker, MG. Leveraging the Massachusetts perinatal quality collaborative to address the COVID-19 pandemic among diverse populations. J Perinatol. 2021. 41:2674-2683. doi:10.1038/s41372-021-01136-0. | Mediators/moderators; Intervention/exposure - KQ3
1125 | Sullivan, MH, Denslow, S, Lorenz, K, Dixon, S, Kelly, E, Foley, KA. Exploration of the Effects of Rural Obstetric Unit Closures on Birth Outcomes in North Carolina. J Rural Health. 2021. 37:373-384. doi:10.1111/jrh.12546. | Independent variable - KQ2; Study participants
1126 | Sun, Y, Sundell, J. Life style and home environment are associated with racial disparities of asthma and allergy in Northeast Texas children. Sci Total Environ. 2011. 409:4229-34. doi:10.1016/j.scitotenv.2011.07.011. | Outcome
1127 | Suna Dağ, Y, Yayan, EH. The Effect of Circular and Oscillating Breast Massage on the Amount of Breast Milk Produced: An Innovative Method. Breastfeed Med. 2022. 17:593-8. doi:10.1089/bfm.2021.0071. | Country; Independent variable - KQ2; Study participants
1128 | Sundquist Beauman, S. Cultural Influences in Infant Feeding. Neonatal Intensive Care. 2019. 32:23-27. | Study design
1129 | Sun-Hee, Kim. Factors associated with Maternal Attachment of Breastfeeding Mothers. Child Health Nursing Research. 2019. 25:65-73. doi:10.4094/chnr.2019.25.1.65. | Country
1130 | Sutherland, T, Pierce, C, Blomquist, J, Handa, V. Breastfeeding Practices Among First-Time Mothers and Across Multiple Pregnancies. Maternal & Child Health Journal. 2012. 16:1665-1671. doi:10.1007/s10995-011-0866-x. | Mediators/moderators; Intervention/exposure - KQ3
1131 | Sutter, C, Fiese, BH, Lundquist, A, Davis, EC, McBride, BA, Donovan, SM. Sources of Information and Support for Breastfeeding: Alignment with Centers for Disease Control and Prevention Strategies. Breastfeed Med. 2018. 13:598-606. doi:10.1089/bfm.2018.0056. | Study participants
1132 | Sutter, C, Davis, EC, Lundquist, A, Koress, V, Isberg, K, Bryant-Cromwell, M, Meline, B, McBride, BA, Fiese, BH. Breastfeeding Information and Support Across Multiple Sources: Identifying Opportunities for Coordinated Care. Clinical Lactation. 2020. 11:84-92. doi:10.1891/CLINLACT-D-19-00017. | Study participants
1133 | Sutter, MB, Gopman, S, Leeman, L. Patient-centered Care to Address Barriers for Pregnant Women with Opioid Dependence. Obstetrics and Gynecology Clinics of North America. 2017. 44:95-+. doi:10.1016/j.ogc.2016.11.004. | Study design
1134 | Syam, A, Abdul-Mumin, KH, Iskandar, I. What Mother, Midwives, and Traditional Birth Helper Said About Early Initiation of Breastfeeding in Buginese-Bajo Culture. SAGE Open Nurs. 2021. 7:23779608211040287. doi:10.1177/23779608211040287. | Country
1135 | Taveras, EM, Gillman, MW, Kleinman, K, Rich-Edwards, JW, Rifas-Shiman, SL. Racial/ethnic differences in early-life risk factors for childhood obesity. Pediatrics. 2010. 125:686-95. doi:10.1542/peds.2009-2100. | Mediators/moderators; Intervention/exposure - KQ3
1136 | Taylor, EC, Nickel, NC, Labbok, MH. Implementing the Ten Steps for Successful Breastfeeding in hospitals serving low-wealth patients. Am J Public Health. 2012. 102:2262-8. doi:10.2105/ajph.2012.300769. | Study participants
1137 | Teles, MAB, Ferreira da Silva Junior, R, Gualberto dos Santos Júnior, G, Prates Fonseca, M, Karoline Eugênio, K. Knowledge And Practices Of Breastfeeding Of Users From The Family Health Strategy. Journal of Nursing UFPE / Revista de Enfermagem UFPE. 2017. 11:2302-2308. doi:10.5205/reuol.10827-96111-1-ED.1106201707. | Country
1138 | Temple Newhook, J, Newhook, LA, Midodzi, WK, Murphy Goodridge, J, Burrage, L, Gill, N, Halfyard, B, Twells, L. Poverty and Breastfeeding: Comparing Determinants of Early Breastfeeding Cessation Incidence in Socioeconomically Marginalized and Privileged Populations in the FiNaL Study. Health Equity. 2017. 1:96-102. doi:10.1089/heq.2016.0028. | Country
1139 | Tender, JA, Janakiram, J, Arce, E, Mason, R, Jordan, T, Marsh, J, Kin, S, Jianping, He, Moon, RY. Reasons for in-hospital formula supplementation of breastfed infants from low-income families. J Hum Lact. 2009. 25:11-7. doi:10.1177/0890334408325821. | Mediators/moderators; Intervention/exposure - KQ3
1140 | Tenfelde, S, Finnegan, L, Hill, PD. Predictors of breastfeeding exclusivity in a WIC sample. J Obstet Gynecol Neonatal Nurs. 2011. 40:179-89. doi:10.1111/j.1552-6909.2011.01224.x. | Mediators/moderators; Intervention/exposure - KQ3
1141 | Tenfelde, SM. Predictors of breastfeeding exclusivity and duration in a sample of WIC participants. University of Illinois at Chicago; 2009. | Publication status
1142 | Tenfelde, SM, Finnegan, L, Miller, AM, Hill, PD. Risk of breastfeeding cessation among low-income women, infants, and children: a discrete time survival analysis. Nurs Res. 2012. 61:86-95. doi:10.1097/NNR.0b013e3182456b0a. | Mediators/moderators; Intervention/exposure - KQ3
1143 | Thomas, C, O’Riordan, MA, Furman, L. Effect of the Knowledge and Attitudes of a Support Person on Maternal Feeding Choice. J Hum Lact. 2017. 33:195-204. doi:10.1177/0890334416678821. | Intervention/exposure - KQ3; Comparator - KQ2
1144 | Thomas, EV. “Why Even Bother; They Are Not Going to Do It?” The Structural Roots of Racism and Discrimination in Lactation Care. Qual Health Res. 2018. 28:1050-1064. doi:10.1177/1049732318759491. | Outcome
1145 | Thomas, JR, Shaikh, U. Use of electronic communication by physician breastfeeding experts for support of the breastfeeding mother. Breastfeed Med. 2012. 7:393-6. doi:10.1089/bfm.2011.0133. | Study participants
1146 | Thompson, AL, Adair, LS, Bentley, ME. Pressuring and restrictive feeding styles influence infant feeding and size among a low-income African-American sample. Obesity (Silver Spring). 2013. 21:562-71. doi:10.1002/oby.20091. | Mediators/moderators; Intervention/exposure - KQ3
1147 | Thompson, AL, Bentley, ME. The critical period of infant feeding for the development of early disparities in obesity. Social Science & Medicine. 2013. 97:288-296. doi:10.1016/j.socscimed.2012.12.007. | Outcome
1148 | Thompson, AL, Wasser, H, Nulty, A, Bentley, ME. Feeding style profiles are associated with maternal and infant characteristics and infant feeding practices and weight outcomes in African American mothers and infants. Appetite. 2021. 160:105084. doi:10.1016/j.appet.2020.105084. | Mediators/moderators; Outcome
1149 | Thompson, J. Inequalities in immunisation and breastfeeding by ethnic group. Community Practitioner. 2010. 83:38-38. | Country; Study design
1150 | Thomson, JL, Tussing-Humphreys, LM, Goodman, MH, Landry, AS, Olender, SE. Low rate of initiation and short duration of breastfeeding in a maternal and infant home visiting project targeting rural, Southern, African American women. Int Breastfeed J. 2016. 12:15. doi:10.1186/s13006-017-0108-y. | Intervention/exposure - KQ3; Independent variable - KQ2
1151 | Thorburn, S, De Marco, M. Insurance-based discrimination during prenatal care, labor, and delivery: perceptions of Oregon mothers. Matern Child Health J. 2010. 14:875-85. doi:10.1007/s10995-009-0533-7. | Mediators/moderators; Intervention/exposure - KQ3
1152 | Thorley, V. Biologically normal: What is ‘normal’ and what is an ‘intervention’? Using the right language for breastfeeding. Essence: Newsletter of the Australian Breastfeeding Association. 2018. 54:10-13. | Study design
1153 | Thulier, D, Mercer, J. Variables associated with breastfeeding duration. JOGNN: Journal of Obstetric, Gynecologic & Neonatal Nursing. 2009. 38:259-268. doi:10.1111/j.1552-6909.2009.01021.x. | Study design
1154 | Tluczek, A, Clark, R, McKechnie, AC, Orland, KM, Brown, RL. Task-oriented and bottle feeding adversely affect the quality of mother-infant interactions after abnormal newborn screens. J Dev Behav Pediatr. 2010. 31:414-26. doi:10.1097/DBP.0b013e3181dd5049. | Mediators/moderators; Intervention/exposure - KQ3
1155 | Tombeau Cost, K, Unternaehrer, E, Szatmari, P, Kennedy, J, Steiner, M, Fleming, A, Jonas, W, Dudin, A, Gaudreau, H, Atkinson, L, Meaney, M, Gaudreau, H. Maternal perceptions of paternal investment are associated with relationship satisfaction and breastfeeding duration in humans. Journal of Family Psychology. 2018. 32:1025-1035. doi:10.1037/fam0000468. | Country
1156 | Tomori, C, Palmquist, AE, Dowling, S. Contested moral landscapes: Negotiating breastfeeding stigma in breastmilk sharing, nighttime breastfeeding, and long-term breastfeeding in the U.S. and the U.K. Soc Sci Med. 2016. 168:178-185. doi:10.1016/j.socscimed.2016.09.014. | Study design
1157 | Topolyan, I, Xu, X. Differential effects of mother’s and child’s postnatal WIC participation on breastfeeding. Applied Economics. 2017. 49:2216-2225. doi:10.1080/00036846.2016.1234702. | Mediators/moderators; Study participants
1158 | Torres, JM. Families, markets, and medicalization: the role of paid support for childbirth and breastfeeding. Qual Health Res. 2015. 25:899-911. doi:10.1177/1049732314553991. | Intervention/exposure - KQ3; Independent variable - KQ2; Study participants
1159 | Torres, ME, Smithwick, J, Luchok, KJ, Rodman-Rice, G. Reducing Maternal And Child Health Disparities Among Latino Immigrants In South Carolina Through A Tailored, Culturally Appropriate And Participant-Driven Initiative. Californian Journal of Health Promotion. 2012. 10:1-14. | Outcome
1160 | Tovar, A, Vadiveloo, M, Østbye, T, Benjamin-Neelon, SE. Maternal predictors of infant beverage consumption: results from the Nurture cohort study. Public Health Nutr. 2019. 22:2591-2597. doi:10.1017/s1368980019000934. | Outcome
1161 | Trout, KK, Averbuch, T, Barowski, M. Promoting Breastfeeding Among Obese Women and Women with Gestational Diabetes Mellitus. Current Diabetes Reports. 2011. 11:7-12. doi:10.1007/s11892-010-0159-6. | Study design
1162 | Trudnak, TE, Arboleda, E, Kirby, RS, Perrin, K. Outcomes of Latina women in CenteringPregnancy group prenatal care compared with individual prenatal care. J Midwifery Womens Health. 2013. 58:396-403. doi:10.1111/jmwh.12000. | Study design
1163 | Tua Karing, J, Tracy, A, Gonzales, CR, Nancarrow, AF, Tomayko, EJ, Tominey, S, Escobar, H, McClelland, MM. Breastfeeding, Early Self-Regulation, and Academic Achievement in Kindergarten Among Disadvantaged Children. Matern Child Health J. 2021. 25:1766-1775. doi:10.1007/s10995-021-03193-5. | Outcome
1164 | Tubay, AT, Mansalis, KA, Simpson, MJ, Armitage, NH, Briscoe, G, Potts, Vi. The Effects of Group Prenatal Care on Infant Birthweight and Maternal Well-Being: A Randomized Controlled Trial. Military Medicine. 2019. 184:e440-e446. doi:10.1093/milmed/usy361. | Study participants
1165 | Tucker, EA, Fouts, HN. Connections Between Prenatal Physical Activity and Breastfeeding Decisions. Qualitative Health Research. 2017. 27:700-713. doi:10.1177/1049732316628514. | Independent variable - KQ2; Study participants
1166 | Tully, KP, Holditch-Davis, D, White-Traut, RC, David, R, O’Shea, TM, Geraldo, V. A Test of Kangaroo Care on Preterm Infant Breastfeeding. J Obstet Gynecol Neonatal Nurs. 2016. 45:45-61. doi:10.1016/j.jogn.2015.10.004. | Study Participants
1167 | Turner, PK, Norwood, K. “I had the luxury … ‘: Organizational breastfeeding support as privatized privilege. Human Relations. 2014. 67:849-874. doi:10.1177/0018726713507730. | Intervention/exposure - KQ3; Independent variable - KQ2
1168 | Tuttle, CR, Slavit, WI. Establishing the business case for breastfeeding. Breastfeed Med. 2009. 4 Suppl 1:S59-62. doi:10.1089/bfm.2009.0031. | Outcome
1169 | Tuttle, CR. Defining a new infant feeding paradigm and refocusing research to increase employer promotion of breastfeeding. Breastfeed Med. 2010. 5:227-8. doi:10.1089/bfm.2010.0033. | Study design
1170 | Uchendu, UO, Ikefuna, AN, Emodi, IJ. Exclusive breastfeeding--the relationship between maternal perception and practice. Niger J Clin Pract. 2009. 12:403-6. | Country
1171 | Ukoli, FA, Keefer, C, Carter, A, Cheaves, M, Granderson, C, Yu, H, Samuels, D. The Impact of a Breastfeeding Promotion Intervention on Rapid Weight Gain among African American Infants. J Health Care Poor Underserved. 2021. 32:271-295. doi:10.1353/hpu.2021.0024. | Comparator
1172 | UP11 The Feeding Young Children Study: Preliminary Results from a WIC-based Bottle Weaning Intervention. Journal of Nutrition Education & Behavior. 2012. 44:S83-S83. doi:10.1016/j.jneb.2012.03.202. | Publication status
1173 | Uscher-Pines, L, Ghosh-Dastidar, B, Bogen, DL, Ray, KN, Demirci, JR, Mehrotra, A, Kapinos, KA. Feasibility and Effectiveness of Telelactation Among Rural Breastfeeding Women. Acad Pediatr. 2020. 20:652-659. doi:10.1016/j.acap.2019.10.008. | Mediators/moderators; Study participants
1174 | Uzun, AK, Orhon, FS, Baskan, S, Ulukol, B. A comparison between adolescent mothers and adult mothers in terms of maternal and infant outcomes at follow-ups. J Matern Fetal Neonatal Med. 2013. 26:454-8. doi:10.3109/14767058.2012.733748. | Country
1175 | Vaaler, ML, Stagg, J, Parks, SE, Erickson, T, Castrucci, BC. Breast-feeding attitudes and behavior among WIC mothers in Texas. J Nutr Educ Behav. 2010. 42:S30-8. doi:10.1016/j.jneb.2010.02.001. | Mediators/moderators; Intervention/exposure - KQ3
1176 | Valero-Chillerón, MJ, Mena-Tudela, D, Cervera-Gasch, Á, González-Chordá, VM, Soriano-Vidal, FJ, Quesada, JA, Castro-Sánchez, E, Vila-Candel, R. Influence of Health Literacy on Maintenance of Exclusive Breastfeeding at 6 Months Postpartum: A Multicentre Study. Int J Environ Res Public Health. 2022. 19:5411. doi:10.3390/ijerph19095411. | Country
1177 | Van Zandt, SE, Kim, S, Erickson, A. Nursing Student Birth Doulas’ Influence On the Childbearing Outcomes of Vulnerable Populations. J Community Health Nurs. 2016. 33:128-38. doi:10.1080/07370016.2016.1191869. | Independent variable - KQ2; Comparator - KQ3
1178 | Vandyousefi, S, Messito, MJ, Katzow, MW, Scott, MA, Gross, RS. Infant appetite traits, feeding practices and child obesity in low-income Hispanic families. Pediatr Obes. 2022. 17:e12913. doi:10.1111/ijpo.12913. | Mediators/moderators; Intervention/exposure - KQ3
1179 | Vasquez, MJ, Berg, OR. The Baby-Friendly journey in a US public hospital. J Perinat Neonatal Nurs. 2012. 26:37-46. doi:10.1097/JPN.0b013e3182107179. | Study participants
1180 | Vaughan, K, McMurray, A, Sidebotham, M, Gamble, J. Factors Influencing International Board Certified Lactation Consultants to Continue Advancing Practice Beyond Certification: A Multinational Study. International Journal of Childbirth. 2017. 7:227-237. doi:10.1891/2156-5295.7.4.170. | Outcome; Study participants
1181 | Vedam, S, Stoll, K, MacDorman, M, Declercq, E, Cramer, R, Cheyney, M, Fisher, T, Butt, E, Yang, YT, Powell Kennedy, H. Mapping integration of midwives across the United States: Impact on access, equity, and outcomes. PLoS One. 2018. 13:e0192523. doi:10.1371/journal.pone.0192523. | Mediators/moderators; Study participants
1182 | Ventura, AK, Teitelbaum, S. Maternal Distraction During Breast- and Bottle Feeding Among WIC and non-WIC Mothers. J Nutr Educ Behav. 2017. 49:S169-S176.e1. doi:10.1016/j.jneb.2017.04.004. | Outcome
1183 | Verma, A, Maria, A, Pandey, RM, Hans, C, Verma, A, Sherwani, F. Family-Centered Care to Complement Care of Sick Newborns: A Randomized Controlled Trial. Indian Pediatr. 2017. 54:455-459. doi:10.1007/s13312-017-1047-9. | Country
1184 | Vieira, GO, de Oliveira Vieira, T, da Cruz Martins, C, de Santana Xavier Ramos, M, Giugliani, ERJ. Risk factors for and protective factors against breastfeeding interruption before 2 years: a birth cohort study. BMC Pediatr. 2021. 21:310. doi:10.1186/s12887-021-02777-y. | Country
1185 | Villalobos, AV, Davis, C, Turner, MM, Long, S, Hull, S, Lapinski, MK. Breastfeeding in Context: African American Women’s Normative Referents, Salient Identities, and Perceived Social Norms. Health Education & Behavior. 2021. 48:496-506. doi:10.1177/10901981211014445. | Intervention/exposure - KQ3; Outcome
1186 | Villalobos, AVK, Turner, MM, Lapinski, MK, Hull, S, Long, S, Wang, J, Moore, EWG. Predicting Breastfeeding Intentions: A Test and Extension of the Theory of Normative Social Behavior with African American Social Identity. Health Commun. 2021. 1-13. doi:10.1080/10410236.2021.1936750. | Outcome
1187 | Vital signs. Different attitudes toward breastfeeding linked to race. Minority Nurse. 2010. 8-8. | Study design; Other (Summary of peer reviewed article)
1188 | Vlasblom, E, van Grieken, A, Beltman, M, L’Hoir, MP, Raat, H, Boere-Boonekamp, MM. Parenting support to prevent overweight during regular well-child visits in 0-3 year old children (BBOFT+ program), a cluster randomized trial on the effectiveness on child BMI and health behaviors and parenting. PLoS One. 2020. 15:e0237564. doi:10.1371/journal.pone.0237564. | Country
1189 | von Ash, T, Alikhani, A, Lebron, C, Risica, PM. Racial/ethnic differences in maternal feeding practices and beliefs at 6 months postpartum. Public Health Nutr. 2022. 25:1-10. doi:10.1017/s1368980021005073. | Outcome
1190 | Wagner, CL, Boan, AD, Marzolf, A, Finch, CW, Morella, K, Guille, C, Gardner, Z, Marriott, BP. The Safety of Mother’s Milk® Tea: Results of a Randomized Double-Blind, Controlled Study in Fully Breastfeeding Mothers and Their Infants. J Hum Lact. 2019. 35:248-260. doi:10.1177/0890334418787474. | Mediators/moderators; Study participants
1191 | Waite, WM, Christakis, D. Relationship of maternal perceptions of workplace breastfeeding support and job satisfaction. Breastfeed Med. 2015. 10:222-7. doi:10.1089/bfm.2014.0151. | Intervention/exposure - KQ3; Independent variable - KQ2; Study participants
1192 | Waite, WM, Christakis, D. The Impact of Mailed Samples of Infant Formula on Breastfeeding Rates. Breastfeed Med. 2016. 11:21-5. doi:10.1089/bfm.2015.0099. | Independent variable - KQ2; Study participants
1193 | Waite, WM, Taylor, JA. Phototherapy for the Treatment of Neonatal Jaundice and Breastfeeding Duration and Exclusivity. Breastfeed Med. 2016. 11:180-5. doi:10.1089/bfm.2015.0170. | Mediators/moderators; Intervention/exposure - KQ3
1194 | Waldrop, J. Exploration of reasons for feeding choices in Hispanic mothers. MCN Am J Matern Child Nurs. 2013. 38:282-8. doi:10.1097/NMC.0b013e31829a5625. | Outcome
1195 | Walker, J, Huria, A, Buckman, C, Tumin, D. The Influence of a Sister’s Breastfeeding Experience on a Mother’s Breastfeeding Behavior: Is There an Intragenerational Effect?. Breastfeed Med. 2021. 16:863-868. doi:10.1089/bfm.2021.0108. | Mediators/moderators; Intervention/exposure - KQ3
1196 | Walker, LO, Sterling, BS, Guy, S, Mahometa, MJ. Cumulative poor psychosocial and behavioral health among low-income women at 6 weeks postpartum. Nurs Res. 2013. 62:233-42. doi:10.1097/NNR.0b013e31829499ac. | Outcome
1197 | Walker, LO. Low-income women’s reproductive weight patterns empirically based clusters of prepregnant, gestational, and postpartum weights. Womens Health Issues. 2009. 19:398-405. doi:10.1016/j.whi.2009.08.003. | Mediators/moderators; Intervention/exposure - KQ3
1198 | Walker, TC, Keene, SD, Patel, RM. Early feeding factors associated with exclusive versus partial human milk feeding in neonates receiving intensive care. J Perinatol. 2014. 34:606-10. doi:10.1038/jp.2014.63. | Study Participants
1199 | Walkup, JT, Barlow, A, Mullany, BC, Pan, W, Goklish, N, Hasting, R, Cowboy, B, Fields, P, Baker, EV, Speakman, K, Ginsburg, G, Reid, R. Randomized controlled trial of a paraprofessional-delivered in-home intervention for young reservation-based American Indian mothers. J Am Acad Child Adolesc Psychiatry. 2009. 48:591-601. doi:10.1097/CHI.0b013e3181a0ab86. | Outcome
1200 | Wallace, LouiseM, Law, SusanM, Joshi, Puja, Hughes, Elizabeth. An organisation-wide approach to training community practitioners in breastfeeding. Community Practitioner. 2011. 84:31-34. | Country
1201 | Wallenborn, J, Masho, S, Ratliff, S. Paternal Pregnancy Intention and Breastfeeding Duration: Findings from the National Survey of Family Growth. Maternal & Child Health Journal. 2017. 21:554-561. doi:10.1007/s10995-016-2139-1. | Mediators/moderators; Intervention/exposure - KQ3
1202 | Wallenborn, JT, Masho, SW. The Interrelationship Between Repeat Cesarean Section, Smoking Status, and Breastfeeding Duration. Breastfeed Med. 2016. 11:440-447. doi:10.1089/bfm.2015.0165. | Mediators/moderators; Intervention/exposure - KQ3
1203 | Wallenborn, JT, Perera, RA, Wheeler, DC, Lu, J, Masho, SW. Workplace support and breastfeeding duration: The mediating effect of breastfeeding intention and self-efficacy. Birth. 2019. 46:121-128. doi:10.1111/birt.12377. | Mediators/moderators; Intervention/exposure - KQ3; Study participants
1204 | Waller, J, Bower, KM, Spence, M, Kavanagh, KF. Using grounded theory methodology to conceptualize the mother-infant communication dynamic: potential application to compliance with infant feeding recommendations. Matern Child Nutr. 2015. 11:749-60. doi:10.1111/mcn.12056. | Mediators/moderators; Intervention/exposure - KQ3; Study participants
1205 | Wallwiener, S, Müller, M, Doster, A, Plewniok, K, Wallwiener, CW, Fluhr, H, Feller, S, Brucker, SY, Wallwiener, M, Reck, C. Predictors of impaired breastfeeding initiation and maintenance in a diverse sample: what is important?. Arch Gynecol Obstet. 2016. 294:455-66. doi:10.1007/s00404-015-3994-5. | Country
1206 | Walsh, EG. Health Disparities: Breastfeeding’s Role in Closing the Gap. Breastfeeding Medicine. 2012. 7:348-349. | Study design
1207 | Walton, LM, Raigangar, V, Abraham, MS, Buddy, C, Hernandez, M, Krivak, G, Caceras, R. Effects of an 8-week pelvic core stability and nutrition community programme on maternal health outcomes. Physiother Res Int. 2019. 24:e1780. doi:10.1002/pri.1780. | Mediators/moderators; Comparator - KQ3
1208 | Walton, S, Roberson, K, Onsomu, EO, Hall, Susan, Dearman, Cathy. Evaluating Centering group prenatal care in rural women with low socioeconomic status to promote access to care and improve pregnancy outcomes. Journal of Public Health (09431853). 2021. 29:285-291. doi:10.1007/s10389-019-01121-0. | Independent variable - KQ2; Study participants
1209 | Wambach, K, Britt, E. Breastfeeding Support Experiences of Registered Nurses in a Large Children’s Hospital System. J Obstet Gynecol Neonatal Nurs. 2018. 47:632-640. doi:10.1016/j.jogn.2018.07.007. | Study participants
1210 | Wambach, KA, Aaronson, L, Breedlove, G, Domian, EW, Rojjanasrirat, W, Yeh, HW. A randomized controlled trial of breastfeeding support and education for adolescent mothers. West J Nurs Res. 2011. 33:486-505. doi:10.1177/0193945910380408. | Mediators/moderators; Study participants
1211 | Wang, L, Grissom, M. Breastfeeding: When “Baby-Friendly” Isn’t Necessarily “Mother-Friendly”. Family Doctor: A Journal of the New York State Academy of Family Physicians. 2019. 7:24-26. | Study design
1212 | Wang, S, Guendelman, S, Harley, K, Eskenazi, B. When Fathers are Perceived to Share in the Maternal Decision to Breastfeed: Outcomes from the Infant Feeding Practices Study II. Matern Child Health J. 2018. 22:1676-1684. doi:10.1007/s10995-018-2566-2. | Intervention/exposure - KQ3; Independent variable - KQ2
1213 | Wang, Y, You, HX, Luo, BR. Exploring the breastfeeding knowledge level and its influencing factors of pregnant women with gestational diabetes mellitus. BMC Pregnancy Childbirth. 2020. 20:723. doi:10.1186/s12884-020-03430-9. | Country
1214 | Ward, LP, Tonnis, R, Otuneye, AT, Clemens, N, Akinbi, H, Morrow, AL. Impact of Institutional Breastfeeding Support in Very Low-Birth Weight Infants. Breastfeed Med. 2021. 16:238-244. doi:10.1089/bfm.2020.0137. | Mediators/moderators; Study participants
1215 | Ware, JL, Love, D, Ladipo, J, Paddy, K, Starr, M, Gilliam, J, Miles, N, Leatherwood, S, Reese, L, Baker, T. African American Breastfeeding Peer Support: All Moms Empowered to Nurse. Breastfeed Med. 2021. 16:156-164. doi:10.1089/bfm.2020.0323. | Mediators/moderators; Comparator - KQ3; Study participants
1216 | Ware, JL, Mzayek, F, Levy, M. Lessons Learned in a Breastfeeding Media Campaign. Breastfeed Med. 2016. 11:380-5. doi:10.1089/bfm.2016.0047. | Outcome
1217 | Ware, JL, Webb, L, Levy, M. Barriers to breastfeeding in the African American population of Shelby County, Tennessee. Breastfeed Med. 2014. 9:385-92. doi:10.1089/bfm.2014.0006. | Intervention/exposure - KQ3; Independent variable - KQ2
1218 | Washio, Y, Collins, BN, Hunt-Johnson, A, Zhang, ZG, Herrine, G, Hoffman, M, Kilby, L, Chapman, D, Furman, LM. Individual breastfeeding support with contingent incentives for low-income mothers in the USA: the ‘BOOST (Breastfeeding Onset & Onward with Support Tools)’ randomised controlled trial protocol. Bmj Open. 2020. 10:8. doi:10.1136/bmjopen-2019-034510. | Publication status; Other (Protocol)
1219 | Washio, Yukiko, Humphreys, Mara, Zeigler, Dianne. Staff acceptability of contingency management to promote longer breastfeeding duration at WIC. Drug & Alcohol Dependence. 2015. 156:e235-e235. doi:10.1016/j.drugalcdep.2015.07.632. | Publication status
1220 | Wasser, HM, Thompson, AL, Siega-Riz, AM, Adair, LS, Hodges, EA, Bentley, ME. Who’s feeding baby? Non-maternal involvement in feeding and its association with dietary intakes among infants and toddlers. Appetite. 2013. 71:7-15. doi:10.1016/j.appet.2013.06.096. | Mediators/moderators; Intervention/exposure - KQ3
1221 | Wasser, HM, Thompson, AL, Suchindran, CM, Hodges, EA, Goldman, BD, Perrin, EM, Faith, MS, Bulik, CM, Heinig, MJ, Bentley, ME. Family-based obesity prevention for infants: Design of the “Mothers & Others” randomized trial. Contemp Clin Trials. 2017. 60:24-33. doi:10.1016/j.cct.2017.06.002. | Publication status; Other (Protocol)
1222 | Watkins, AL, Dodgson, JE. A geographic comparison of breastfeeding duration and resources for low income women. Communicating Nursing Research. 2010. 43:390-390. | Publication status
1223 | Way, S, Taylor, A, Miller, J. Infant Nutrition. Supporting breastfeeding: it takes a whole community. MIDIRS Midwifery Digest. 2015. 25:491-492. | Country; Study design
1224 | Weddig, J. Improving breastfeeding initiation practices of registered nurses through online theory-based education. Colorado State University; 2011. | Publication status
1225 | Wee, PH, Loy, SL, Toh, JY, Tham, EKH, Cheung, YB, Godfrey, KM, Gluckman, PD, Saw, SM, Chong, YS, Lek, N, Chan, JKY, Goh, DYT, Chong, MF, Yap, F. Circadian feeding patterns of 12-month-old infants. Br J Nutr. 2017. 117:1702-1710. doi:10.1017/s0007114517001684. | Country
1226 | Wegienka, G, Havstad, S, Joseph, CL, Zoratti, E, Ownby, D, Woodcroft, K, Johnson, CC. Racial disparities in allergic outcomes in African Americans emerge as early as age 2 years. Clin Exp Allergy. 2012. 42:909-17. doi:10.1111/j.1365-2222.2011.03946.x. | Outcome
1227 | Weikel, BW, Palau, MA, Hwang, SS. Ethnic Disparities in the Care of Opioid-Exposed Newborns in Colorado Birthing Hospitals. Hosp Pediatr. 2021. 11:1190-1198. doi:10.1542/hpeds.2021-005824. | Mediators/moderators; Intervention/exposure - KQ3
1228 | Weinfield, NS, Anderson, CE. Postpartum Symptoms of Depression are Related to Infant Feeding Practices in a National WIC Sample. J Nutr Educ Behav. 2022. 54:118-124. doi:10.1016/j.jneb.2021.09.002. | Outcome
1229 | Weldon, RH, Webster, M, Harley, KG, Bradman, A, Fenster, L, Davis, MD, Hubbard, A, Barr, DB, Holland, N, Eskenazi, B. Serum persistent organic pollutants and duration of lactation among Mexican-American women. J Environ Public Health. 2010. 2010:861757. doi:10.1155/2010/861757. | Mediators/moderators; Intervention/exposure - KQ3
1230 | Wen, X, Kong, KL, Eiden, RD, Sharma, NN, Xie, C. Sociodemographic differences and infant dietary patterns. Pediatrics. 2014. 134:e1387-98. doi:10.1542/peds.2014-1045. | Outcome
1231 | Wessells, A, Smith, C, Gladney, J. Lactation Care: Advocating for Equitable Access at the Ohio Department of Medicaid. Clinical Lactation. 2020. 11:130-140. doi:10.1891/CLINLACT-D-19-00031. | Study participants
1232 | Whaley, SE, Koleilat, M, Whaley, M, Gomez, J, Meehan, K, Saluja, K. Impact of policy changes on infant feeding decisions among low-income women participating in the Special Supplemental Nutrition Program for Women, Infants, and Children. Am J Public Health. 2012. 102:2269-73. doi:10.2105/ajph.2012.300770. | Outcome
1233 | Whipps, MD. Education Attainment and Parity Explain the Relationship Between Maternal Age and Breastfeeding Duration in U.S. Mothers. J Hum Lact. 2017. 33:220-224. doi:10.1177/0890334416679385. | Mediators/moderators; Intervention/exposure - KQ3
1234 | Whipps, MDM, Iqbal, Y. Feeling Better, Doing Worse: “Mommy Wars” Infant Formula Advertising, Collective Action, and Breastfeeding Inequities. J Hum Lact. 2021. 37:343-347. doi:10.1177/0890334420940643. | Outcome
1235 | Whipps, MDM, Miller, EB, Bogen, DL, Mendelsohn, AL, Morris, PA, Shaw, D, Gross, RS. Breastfeeding Behaviors and Maternal Interaction Quality in a Low-Income, Ethnic Minority Population. J Dev Behav Pediatr. 2020. 41:180-186. doi:10.1097/dbp.0000000000000743. | Intervention/exposure - KQ3; Independent variable - KQ2
1236 | Whipps, MDM, Yoshikawa, H, Demirci, JR, Hill, J. “Painful, yet Beautiful, Moments”: Pathways Through Infant Feeding and Dynamic Conceptions of Breastfeeding Success. Qual Health Res. 2022. 32:31-47. doi:10.1177/10497323211032158. | Independent variable - KQ2; Study participants
1237 | Whipps, MDM, Yoshikawa, H, Demirci, JR. Latent trajectories of infant breast milk consumption in the United States. Matern Child Nutr. 2019. 15:e12655. doi:10.1111/mcn.12655. | Outcome
1238 | White, BK, Burns, SK, Giglia, RC, Scott, JA. Designing evaluation plans for health promotion mHealth interventions: a case study of the Milk Man mobile app. Health Promotion Journal of Australia. 2016. 27:198-203. doi:10.1071/HE16041. | Country; Outcome
1239 | White, BC. The 7-Year Journey of a Breastfeeding Black Woman. Clinical Lactation. 2021. 12:56-57. doi:10.1891/CLINLACT-D-21-00008. | Study design
1240 | White, JA. Equity and Social Justice Within African American Breastfeeding Approaches. Breastfeed Med. 2014. 9:1-2. doi:10.1089/bfm.2014.0075. | Outcome; Study design
1241 | White, LG, Devane-Johnson, S. Increasing Breastfeeding Rates in Black Women by Increasing Black Health Professionals. Journal for Nurse Practitioners. 2020. 16:89-89. doi:10.1016/j.nurpra.2019.07.010. | Study design
1242 | White, VA. The state maternal and child health/title v agencies support breastfeeding: surveillance and programs. Breastfeeding Medicine. 2010. 5:241-242. doi:10.1089/bfm.2010.0030. | Outcome; Study participants
1243 | Wiener, RC, Wiener, MA. Breastfeeding prevalence and distribution in the USA and Appalachia by rural and urban setting. Rural Remote Health. 2011. 11:1713. | Independent variable - KQ2; Study participants
1244 | Wilhelm, S, Rodehorst-Weber, K, Aguirre, T, Stepans, MB, Hertzog, M, Clarke, M, Herboldsheimer, A. Lessons learned conducting breastfeeding intervention research in two northern plains tribal communities. Breastfeed Med. 2012. 7:167-72. doi:10.1089/bfm.2011.0036. | Outcome
1245 | Wilhelm, S, Aguirre, T. Feasibility of a Bilingual, Interactive, Computer-Based Breastfeeding Support Program for Rural Hispanic Women. JOGNN: Journal of Obstetric, Gynecologic & Neonatal Nursing. 2015. 44:S60-S60. doi:10.1111/1552-6909.12631. | Publication status
1246 | Williams, A, Young, J, Kearney, L, Keogh, S. Improving knowledge of breastfeeding management: a practice development intervention for paediatric nurses. Neonatal, Paediatric & Child Health Nursing. 2013. 16:8-14. | Country
1247 | Williams, CB, LaCoursiere, DY, Talavera, GA, Gahagan, S. A Feasibility Study to Promote Optimal Weight in First Time Pregnant Mothers and Their Babies: Lessons Learned in a US-Mexico Border Community. Matern Child Health J. 2019. 23:578-584. doi:10.1007/s10995-018-2685-9. | Outcome
1248 | Williams, CM, Cprek, S, Asaolu, I, English, B, Jewell, T, Smith, K, Robl, J. Kentucky Health Access Nurturing Development Services Home Visiting Program Improves Maternal and Child Health. Matern Child Health J. 2017. 21:1166-1174. doi:10.1007/s10995-016-2215-6. | Mediators/moderators; Study participants
1249 | Williams, K, Kurz, T, Summers, M, Crabb, S. Discursive constructions of infant feeding: The dilemma of mothers’ “guilt’. Feminism & Psychology. 2013. 23:339-358. doi:10.1177/0959353512444426. | Outcome
1250 | Wilson, JC. The Male Perspective on Breastfeeding. JOGNN: Journal of Obstetric, Gynecologic & Neonatal Nursing. 2017. 46:S58-S58. doi:10.1016/j.jogn.2017.04.084. | Publication status
1251 | Wilson, JC. Using Social Media for Breastfeeding Support. Nursing for Women’s Health. 2020. 24:332-343. doi:10.1016/j.nwh.2020.07.003. | Intervention/exposure - KQ3; Independent variable - KQ2
1252 | Wilson, MJ, MacArthur, C, Cooper, GM, Bick, D, Moore, PA, Shennan, A. Epidural analgesia and breastfeeding: a randomised controlled trial of epidural techniques with and without fentanyl and a non-epidural comparison group. Anaesthesia. 2010. 65:145-53. doi:10.1111/j.1365-2044.2009.06136.x. | Country
1253 | Witt, AM, Witt, R, Lasko, L, Flocke, S. Translating Team-Based Breastfeeding Support into Primary Care Practice. J Am Board Fam Med. 2019. 32:818-826. doi:10.3122/jabfm.2019.06.190118. | Mediators/moderators; Comparator - KQ3; Study participants
1254 | Witt, R, Vatti, T, Lasko, L, Witt, AM. Team-Based Breastfeeding Support at a Federally Qualified Health Center: Efficacy, Utilization, and Patient Satisfaction. Breastfeed Med. 2021. 16:741-749. doi:10.1089/bfm.2021.0009. | Mediators/moderators; Study participants
1255 | Wojcicki, JM, Gugig, R, Tran, C, Kathiravan, S, Holbrook, K, Heyman, MB. Early exclusive breastfeeding and maternal attitudes towards infant feeding in a population of new mothers in San Francisco, California. Breastfeed Med. 2010. 5:9-15. doi:10.1089/bfm.2009.0003. | Mediators/moderators; Intervention/exposure - KQ3
1256 | Wojcicki, JM, Heyman, MB, Elwan, D, Lin, J, Blackburn, E, Epel, E. Early exclusive breastfeeding is associated with longer telomeres in Latino preschool children. Am J Clin Nutr. 2016. 104:397-405. doi:10.3945/ajcn.115.115428. | Outcome
1257 | Wood, NK, Sanders, EA. Mothers With Perceived Insufficient Milk: Preliminary Evidence of Home Interventions to Boost Mother–Infant Interactions. Western Journal of Nursing Research. 2018. 40:1184-1202. doi:10.1177/0193945916687552. | Mediators/moderators; Study participants
1258 | Worobey, J. Why Some Mothers Stop Breast-Feeding: Self-reported Reasons for Switching to Formula. Topics in Clinical Nutrition. 2011. 26:228-233. doi:10.1097/TIN.0b013e3182260d9b. | Comparator - KQ2; Study participants
1259 | Wouk, K, Chetwynd, E, Vitaglione, T, Sullivan, C. Improving Access to Medical Lactation Support and Counseling: Building the Case for Medicaid Reimbursement. Matern Child Health J. 2017. 21:836-844. doi:10.1007/s10995-016-2175-x. | Mediators/moderators; Study participants
1260 | Wright, SS, Lea, CS, Holloman, R, Cornett, A, Harrison, LM, Randolph, GD. Using quality improvement to promote breast-feeding in a local health department. J Public Health Manag Pract. 2012. 18:36-42. doi:10.1097/PHH.0b013e31822d2e3a. | Mediators/moderators; Comparator - KQ3
1261 | Wu, N, McClean, MD, Brown, P, Aschengrau, A, Webster, TF, Wu, Nerissa, McClean, MichaelD, Brown, Phil, Aschengrau, Ann, Webster, ThomasF. Participant experiences in a breastmilk biomonitoring study: a qualitative assessment. Environmental Health: A Global Access Science Source. 2009. 8:4-4. doi:10.1186/1476-069X-8-4. | Independent variable - KQ2; Study participants
1262 | Wu, Tsu-Yin, Ford, Olivia, Rainville, Alice Jo, Bessire, Rachel, Yang, Xining, Jackson-Dyer, Tameka, Haimout, Amaal. Reducing Lactation Support Disparities for a Marginalized Community Through a Policy, Systems, and Environmental Change Approach: A Case Study in Michigan. Journal of Human Lactation. 2022. 38:53-60. doi:10.1177/08903344211066836. | Outcome
1263 | Xiang, AH, Chow, T, Mora-Marquez, J, Martinez, MP, Wang, X, Yu, W, Panganiban, MB, Richter, PM, Schneider, DI. Breastfeeding Persistence at 6 Months: Trends and Disparities from 2008 to 2015. J Pediatr. 2019. 208:169-175.e2. doi:10.1016/j.jpeds.2018.12.055. | Mediators/moderators; Intervention/exposure - KQ3
1264 | Yalçin, SS, Orün, E. Breastfeeding status and maternal psychopathologies: in a longitudinal study. Archives of Disease in Childhood. 2011. 96:900-900. doi:10.1136/adc.2011.214007. | Intervention/exposure - KQ3; Country; Independent variable - KQ2
1265 | Yılmaz, E, Yılmaz, Z, Isık, H, Gultekın, IB, Timur, H, Kara, F, Kucukozkan, T. Factors Associated with Breastfeeding Initiation and Exclusive Breastfeeding Rates in Turkish Adolescent Mothers. Breastfeed Med. 2016. 11:315-320. doi:10.1089/bfm.2016.0012. | Country
1266 | Yin, HS, Sanders, LM, Rothman, RL, Shustak, R, Eden, SK, Shintani, A, Cerra, ME, Cruzatte, EF, Perrin, EM. Parent health literacy and “obesogenic” feeding and physical activity-related infant care behaviors. J Pediatr. 2014. 164:577-83.e1. doi:10.1016/j.jpeds.2013.11.014. | Mediators/moderators; Intervention/exposure - KQ3
1267 | Young, LW, Zhuopei, H, Annett, RD, Das, A, Fuller, JF, Higgins, RD, Lester, BM, Merhar, SL, Simon, AE, Songthip, O, Smith, B, Crawford, MM, Atz, AM, Cottrell, LE, Czynski, AJ, Newman, S, Paul, DA, Sánchez, PJ, Semmens, EO, Smith, CM. Site-Level Variation in the Characteristics and Care of Infants With Neonatal Opioid Withdrawal. Pediatrics. 2021. 147:1-10. doi:10.1542/peds.2020-008839. | Mediators/moderators; Intervention/exposure - KQ3
1268 | Yuksel, A, Bayrakci, H, Yilmaz, EB. Self-efficacy, Psychological Well-Being and Perceived Social Support Levels in Pregnant Women. International Journal of Caring Sciences. 2019. 12:1120-1129. | Country
1269 | Yun, S, Liu, Q, Mertzlufft, K, Kruse, C, White, M, Fuller, P, Zhu, BP. Evaluation of the Missouri WIC (Special Supplemental Nutrition Program for Women, Infants, and Children) breast-feeding peer counselling programme. Public Health Nutr. 2010. 13:229-37. doi:10.1017/s1368980009990668. | Mediators/moderators; Study participants
1270 | Zamora, G, Lutter, CK, Peña-Rosas, JP. Using an Equity Lens in the Implementation of Interventions to Protect, Promote, and Support Optimal Breastfeeding Practices. Journal of Human Lactation. 2015. 31:21-25. doi:10.1177/0890334414561477. | Study design
1271 | Zanardo, V, Cavallin, F, Guerrini, P, Bertin, M, Straface, G. Prepregnancy Body Mass Index Shift Across Gestation: An Association with Breastfeeding Practices?. Breastfeed Med. 2017. 12:615-620. doi:10.1089/bfm.2017.0037. | Country
1272 | Zandoná, B, Matos, S, Bernardi, JR, Goldani, MZ, Kieling, RR, Silva, CHD. Influence of intra- and extrauterine factors on infant sleep in the first 6 months of life. J Pediatr (Rio J). 2021. 97:160-166. doi:10.1016/j.jped.2020.01.007. | Country
1273 | Zellner, H. Question: What is the acceptability and use of donor breast milk among varying cultures and religious practices?. Support Line. 2019. 41:23-24. | Study design
1274 | Zhang, F, Yang, Y, Bai, T, Sun, L, Sun, M, Shi, X, Zhu, M, Ge, M, Xia, H. Effect of pumping pressure on onset of lactation after caesarean section: A randomized controlled study. Matern Child Nutr. 2018. 14:e12486. doi:10.1111/mcn.12486. | Country
1275 | Zhang, Q, Lamichhane, R, Wouk, K, Guthrie, J, Li, K. Prenatal perception of breastfeeding recommendation predicts early breastfeeding outcomes of participants in the Supplemental Nutrition Program for Women, Infants, and Children (WIC). Am J Clin Nutr. 2021. 114:1949-59. doi:10.1093/ajcn/nqab268. | Intervention/exposure - KQ3; Independent variable - KQ2
1276 | Zhang, Y, Carlton, E, Fein, SB. The association of prenatal media marketing exposure recall with breastfeeding intentions, initiation, and duration. J Hum Lact. 2013. 29:500-9. doi:10.1177/0890334413487256. | Mediators/moderators; Study participants
1277 | Zhou, YE, Emerson, JS, Husaini, BA, Hull, PC. Association of Infant Feeding with Adiposity in Early Childhood in a WIC Sample. Journal of Health Care for the Poor and Underserved. 2014. 25:1542-1551. doi:10.1353/hpu.2014.0181. | Outcome
1278 | Zhu, P, Hao, J, Jiang, X, Huang, K, Tao, F. New insight into onset of lactation: mediating the negative effect of multiple perinatal biopsychosocial stress on breastfeeding duration. Breastfeed Med. 2013. 8:151-8. doi:10.1089/bfm.2012.0010. | Country
1279 | Zhu, Y, Hernandez, LM, Mueller, P, Dong, Y, Hirschfeld, S, Forman, MR. Predictive Models for Characterizing Disparities in Exclusive Breastfeeding Performance in a Multi-ethnic Population in the US. Matern Child Health J. 2016. 20:398-407. doi:10.1007/s10995-015-1838-3. | Mediators/moderators; Intervention/exposure - KQ3
1280 | Zhuang, J, Bresnahan, MJ, Yan, X, Zhu, Y, Goldbort, J, Bogdan-Lovis, E. Keep Doing the Good Work: Impact of Coworker and Community Support on Continuation of Breastfeeding. Health Commun. 2019. 34:1270-1278. doi:10.1080/10410236.2018.1476802. | Mediators/moderators; Study participants
1281 | Zimmerman, E, Rodgers, RF, O’Flynn, J, Bourdeau, A. Weight-Related Concerns as Barriers to Exclusive Breastfeeding at 6 Months. J Hum Lact. 2019. 35:284-291. doi:10.1177/0890334418797312. | Intervention/exposure - KQ3; Independent variable - KQ2
1282 | Ziol-Guest, KM, Hernandez, DC. First- and second-trimester WIC participation is associated with lower rates of breastfeeding and early introduction of cow’s milk during infancy. J Am Diet Assoc. 2010. 110:702-9. doi:10.1016/j.jada.2010.02.013. | Mediators/moderators; Study participants
1283 | Zwedberg, S, Naeslund, L. Different attitudes during breastfeeding consultations when infant formula was given: a phenomenographic approach. Int Breastfeed J. 2011. 6:1. doi:10.1186/1746-4358-6-1. | Country

* Abbreviations: KQ2, Key Question 2; KQ3, Key Question 3