# Appendix 4 NIMHD research framework

Figure A-1 presents the National Institute on Minority Health and Health Disparities (NIMHD) research framework. Illustrative examples of factors at each domain and level of influence are provided in the framework; however, these examples are not exhaustive.

Figure A-1 The National Institute on Minority Health and Health Disparities (NIMHD) research framework^*^ * National Institute on Minority Health and Health Disparities (2017). NIMHD Research Framework. Retrieved from https://nimhd.nih.gov/researchFramework (https://nimhd.nih.gov/researchFramework.%20Accessed%20on%20May%2026). Accessed on May 26, 2023.

A picture containing text, screenshot, font, number Description automatically generated