# Appendix 3 Reporting of race and ethnicity

The following tables provide information on how race and ethnicity were examined in each of the included studies for Key Question 2 (Table A-5 and Table A-6) and Key Question 3 (Table A-7).

Table A-5 How race and ethnicity were examined in included articles (Key Question 2, quantitative studies)^*^,^†^

Study | Does the article describe why race and/or ethnicity was important to the research question? | Does the article provide the definition of race and/or ethnicity used in the study?^‡^ | How does the article define race and/or ethnicity? | Does the article specifically report how race and/or ethnicity was measured? | How race and/or ethnicity was measured | Does the article describe how race and/or ethnicity was coded? | How race and/or ethnicity was coded
Abuelezam, 2020^1^ | Yes | No | NR | Yes | Birth certificate; standard two-step question: “Are you Hispanic/Latino/Spanish” and “What is your race?” | Yes | Other (Hispanic, Non-Hispanic Asian, Non-Hispanic Black, Non-Hispanic Other), Non-Hispanic White
Belanoff, 2012^2^ | Yes | No | NR | Yes | Survey | Yes | Non-Hispanic Black, Non-Hispanic Other, Non-Hispanic White
Bramson, 2010^3^ | No | No | NR | Yes | Interviewed by staff | Yes | African American, Caucasian, Hispanic, Other
Buckman, 2020^4^ | No | No | NR | Yes | Birth certificate | Yes | Hispanic, Non-Hispanic Black, Non-Hispanic White, Other
Campbell, 2018^5^ | No | No | NR | Yes | Self-report via survey | Yes | Hispanic, Non-Hispanic Black, Non-Hispanic White
Carlin, 2021^6^ | Yes | No | NR | Yes | Self-identification | Yes | Black/African American, White/Caucasian
Carswell, 2018^7^ | Yes | No | NR | Yes | Self-report at interview | Yes | Non-White, White
Chen, 2016^8^ | Yes | No | NR | Yes | Hospital chart review | Yes | African American, Non-African American
Cheng, 2018^9^ | Yes | No | NR | Yes | Self-report in close-ended survey (“Mark one category that best describes the mother’s race”; “one category that best describes the mother’s ancestry or ethnic heritage”) | Yes | Other Ethnicity (African American, African American, Asian Indian, Brazilian, Cambodian, Cape Verdean, Chinese, Colombian, Dominican, European, Filipino, Haitian, Jamaican, Japanese, Korean, Lebanese, Mexican, Native American, Other, Other Asian/Pacific Islander, Other Central American, Other Hispanic/Latina, Other Middle Eastern, Other Portuguese, Other South American, Other West Indian/Caribbean, Puerto Rican, Salvadoran, Vietnamese), White
Chung, 2021^10^ | Yes | No | NR | Yes | Hospital records | Yes | American Indian/Alaska Native, Asian/Native Hawaiian Or Pacific Islander, Black Or African American, Non-Hispanic, Hispanic, Multi-Race/Other, White, Non-Hispanic
Corsack, 2022^11^ | No | No | NR | Yes | Survey | Yes | Hispanic, Non-Hispanic Black, Non-Hispanic Other, Non-Hispanic White
Dabritz, 2010^12^ | Yes | No | NR | Yes | Survey | Yes | Hispanic, Other Ethnicity, White
Demirci, 2013^13^ | No | No | NR | Yes | Birth certificate | Yes | Black, Other, White
Fabiyi, 2021^14^ | Yes | No | NR | Yes | Survey | Yes | Hispanic, Non-Hispanic Black, Non-Hispanic White
Francescon, 2016^15^ | No | No | NR | Yes | Self-report via survey | Yes | Hispanic, Non-Hispanic Black, Non-Hispanic White, Other
Gertz, 2019^16^ | No | No | NR | Yes | Vital statistics natality birth database | Yes | Hispanic, Non-Hispanic Black, Non-Hispanic White, Other
Glazer, 2022^17^ | Yes | No | NR | Yes | Self-reported via electronic medical record | Yes | Latina, Non-Latina Asian, Non-Latina Black, Non-Latina White, Other/Unknown (Includes American Indian Or Alaska Native, Native Hawaiian Or Pacific Islander, And Other Or Unspecified Race/Ethnicity)
Gyllstrom, 2021^18^ | No | No | NR | Yes | Interviewed by staff | Yes | Black, Hispanic, Other, White
Haile, 2017^19^ | No | No | NR | Yes | Self-report via survey | Yes | Hispanic, Non-Hispanic Black, Non-Hispanic White, Other
Hamilton, 2020^20^ | No | No | NR | Yes | Self-report via questionnaire | Yes | Hispanic, Non-Hispanic Black, Non-Hispanic White, Other (Asian, Chinese, Japanese, Filipino, Hawaiian, Alaskan Native, American Indian, Mixed Race, And Other NonWhite)
Hawkins, 2014^21^ | Yes | No | NR | Yes | Self-report via birth certificate | Yes | Asian/Pacific Islander, Black, Hispanic, Other, White
Hayes, 2014^22^ | Yes | No | NR | Yes | Birth certificate | Yes | Black, Chinese, Filipino, Japanese, Korean, Native Hawaiian, Other/Unknown, Samoan, White
Holland, 2018^23^ | Yes | No | NR | Yes | Self-report via survey | Yes | Black, Hispanic, White
Holmes, 2011^24^ | No | No | NR | Yes | Self-report via survey (close-ended question) | Yes | Black, Hispanic (Mexican-American And Other Hispanic), Other, White
Hughes, 2019^25^ | Yes | No | NR | Yes | Survey | Yes | Mexican, Non-Hispanic Black, Non-Hispanic White, Puerto Rican
Jacobson, 2015^26^ | Yes | No | NR | Yes | Survey | Yes | American Indian, Asian Or Hawaiian/Pacific Islander, Hispanic, Multi-Racial, Non-Hispanic Black, Non-Hispanic White
Jolles, 2022^27^ | Yes | No | NR | Yes | Self-report via survey; mandatory field | Yes | American Indian, Asian, Black, Hispanic, Native Hawaiian/Pacific Islander
Kachoria, 2014a^28^ | Yes | No | NR | Yes | Birth certificate | Yes | Black Non-Hispanic, Hispanic, Other Non-Hispanic, White Non-Hispanic
Kachoria, 2014b^29^ | Yes | No | NR | Yes | Birth certificate | Yes | Black Non-Hispanic, Hispanic, Other Non-Hispanic, White Non-Hispanic
Kirksey, 2021^30^ | Yes | No | NR | Yes | Maternal self-report via survey | Yes | Black, Other (1973: Other; 1982+: Alaskan Native Or American Indian, Asian Or Pacific Islander, Hispanic), White
Kitsantas, 2010^32^ | No | No | NR | No | NR | Yes | Black, Hispanic, Other, White
Kitsantas, 2011^31^ | Yes | No | NR | Yes | Survey | Yes | Hispanic, Non-Hispanic Black, Non-Hispanic White
Kortsmit, 2021^33^ | No | No | NR | Yes | Birth certificate | Yes | Hispanic, Non-Hispanic Black, Non-Hispanic Other, Non-Hispanic White
Krause, 2011^34^ | Yes | No | NR | Yes | Self-report via survey | Yes | Black, White/Other
Kummer, 2020^35^ | Yes | No | NR | Yes | Maternal self-report via telephone survey | Yes | Black Non-Hispanic, Hispanic, Other/Multiracial Non-Hispanic, White Non-Hispanic
Lee, 2009^36^ | Yes | No | NR | Yes | Interviewers using structured questionnaires | Yes | Foreign-Born Black, Non-Hispanic Native-Born Black, Non-Hispanic White, Other Hispanic, Puerto Rican
Liu, 2010^37^ | Yes | No | NR | Yes | Survey | Yes | Black, White
Lundquist, 2015^38^ | Yes | No | NR | Yes | Maternal self-report via survey | Yes | Asian, Black, Latina, Other, White
Lynch, 2012^39^ | Yes | No | NR | Yes | Survey | Yes | Hispanic (Hispanic, Other; Hispanic, American Indian Or Alaskan Native; Hispanic, Black; Hispanic, White), Non-Hispanic Black, Non-Hispanic White
Ma, 2012^40^ | Yes | No | NR | Yes | Self-report via survey | Yes | Black, White
Marshall, 2013^41^ | Yes | No | NR | Yes | Birth certificate | Yes | Non-Hispanic Black, Non-Hispanic White
Masho, 2015^42^ | Yes | No | NR | Yes | Survey | Yes | Hispanic, Non-Hispanic Black, Non-Hispanic Other, Non-Hispanic White
McKinney, 2016^43^ | Yes | No | NR | Yes | Maternal self-report via survey | Yes | Hispanic, Non-Hispanic Black, Non-Hispanic White (Other Or Mixed Race Placed In Either Hispanic Or Black Group Which They Partially Self-Identified)
Mercier, 2018^44^ | Yes | No | NR | Yes | Prenatal and outpatient chart | Yes | African American, Asian, Hispanic, White
Morrow, 2021^45^ | Yes | No | NR | Yes | Obstetrical records | Yes | Non-Hispanic And Biracial, Asian, Native Or Pacific Islander, Non-Hispanic Black, Non-Hispanic White
Nguyen, 2017^46^ | Yes | No | NR | Yes | Self-report via birth certificate | Yes | African American Non-Hispanic, Any Race Hispanic, Asian American Non-Hispanic, Other Race Non-Hispanic, White Non-Hispanic
Ogbuanu, 2011^47^ | No | No | NR | No | NR | Yes | Black Non-Hispanic, Hispanic, Other Non-Hispanic, White Non-Hispanic
Orozco, 2020^48^ | Yes | No | NR | Yes | Self-identified in survey | Yes | Hispanic, Non-Hispanic Black, Non-Hispanic White, Other (American Indians, Pacific Islanders, Asian Americans, Including Multiracial Families)
Pithia, 2021^49^ | Yes | No | NR | Yes | Electronic medical record | Yes | African American, American Indian/Alaska Native, Asian, More Than One Race, Native Hawaiian/Pacific Islander, Other, White Non-Hispanic Maternal Ethnicity (Vs Hispanic)
Safon, 2021^50^ | Yes | No | NR | Yes | Self-identified in survey | Yes | Non-Hispanic Black, Non-Hispanic White
Shafer, 2017^51^ | Yes | No | NR | Yes | Self-identified with close-ended options | Yes | American Indian, Alaska Native, Black, Chinese, Filipino, Japanese, Mixed Race, Native Hawaiian, Other Asian, Other Non-White, White
Sipsma, 2013^52^ | No | No | NR | Yes | Interviewed by staff | Yes | Black, Hispanic Latino (Partner Only), Non-Hispanic, White/Other
Sparks, 2010^53^ | Yes | No | NR | Yes | Parental interview and birth certificate | Yes | Asian (Of All Ethnicities), Foreign-Born Mexican Origin Hispanic, Native Americans, Non-Hispanic Black, Non-Hispanic White, Other Hispanic (Including Puerto Ricans And Cubans), U.S.-Born Mexican Origin Hispanic
Sparks, 2011^54^ | Yes | No | NR | Yes | Self-identified from parental interview | Yes | Asian, Foreign-Born Mexican-Origin Hispanic, Native American, Non-Hispanic Black, Non-Hispanic White, Other Hispanic, U.S.-Born Mexican-Origin Hispanic
Stevens, 2019^55^ | Yes | No | NR | No | NR | Yes | Hispanic, Non-Hispanic Black, Non-Hispanic White
Tanda, 2018^56^ | No | No | NR | Yes | Survey | Yes | Hispanic, Non-Hispanic Black, Non-Hispanic White, Others
Thompson, 2013^57^ | Yes | No | NR | Yes | Birth certificate | Yes | Black, Hispanic, Other, White
Walker, 2014^58^ | Yes | No | NR | Yes | Birth certificate; women reported a single Hispanic ethnic subgroup and non-Hispanic White women designated a single race | Yes | Hispanic (Mexican, Puerto Rican, Cuban, Or Other Hispanic), Non-Hispanic White
Wallenborn, 2017a^61^ | No | No | NR | Yes | Survey | Yes | Hispanic, Non-Hispanic Black, Non-Hispanic Other, Non-Hispanic White
Wallenborn, 2017b^62^ | Yes | No | NR | Yes | Mailed questionnaires | Yes | Black, Hispanic Other Including Asian/Pacific Islander, White
Wallenborn, 2018^59^ | No | No | NR | Yes | Vital statistics natality birth database | Yes | Hispanic, Non-Hispanic Black, Non-Hispanic Multiracial, Non-Hispanic Other, Non-Hispanic White
Wallenborn, 2019^60^ | Yes | No | NR | Yes | Vital statistics natality birth database | Yes | Hispanic, Non-Hispanic Black, Non-Hispanic White
Weiser, 2009^63^ | No | No | NR | Yes | Survey | Yes | Black, White, Other
White, 2022^64^ | Yes | No | NR | Yes | Self-report via Questionnaire | Yes | Hispanic, Non-Hispanic Black, Non-Hispanic Other (Asian, Native American, Other)
Whitley, 2021^66^ | Yes | Yes | Social construct | Yes | Maternal self-report via survey (close-ended and select up to three races; first race mentioned used) | Yes | Black, Other Races (Latino/Hispanic, Asian, Native Hawaiian Or Pacific Islander, Other), White
Whitley, 2022^65^ | Yes | Yes | Social construct | Yes | Self-report via survey (close-ended question and could select up to three races); separate question about Latino/Hispanic ethnicity. | Yes | Black (Non-Hispanic), Other (Asian, Native Hawaiian Or Pacific Islander, Other, Latino/Hispanic), White (Non-Hispanic)
Wiener, 2016^67^ | Yes | No | NR | Yes | Survey | Yes | Hispanic, Non-Hispanic Black, Non-Hispanic White
Wouk, 2017^68^ | Yes | No | NR | Yes | Survey | Yes | Asian, Black, Hispanic, Other, White
Yourkavitch, 2018^69^ | Yes | No | NR | Yes | Electronic birth certificate | Yes | Asian/Pacific Islander, Black, Hispanic, White
Yu, 2013^70^ | Yes | No | NR | Yes | Survey | Yes | Hispanic, Multirace, Non-Hispanic Black, Non-Hispanic White, Other
Zhang, 2021^71^ | No | No | NR | Yes | Self-report via telephone survey | Yes | Hispanic, Non-Hispanic Black, Non-Hispanic, White

* Abbreviations: NR, not reported; vs, versus

† Questions used to assess how race and ethnicity were examined adapted from: Martinez RAM, Andrabi N, Goodwin AN, Wilbur RE, Smith NR, Zivich PN. Resource Packet for “Clear communication of race and ethnicity for public health: best practices & common failings”. 2021. doi: 10.17615/dcfj-9g46

‡ e.g., social construct, biological construct

Table A-6 How race and ethnicity were examined in included articles (Key Question 2, qualitative studies)^*^,^†^

Study | Does the article describe why race and/or ethnicity was important to the research question? | Does the article provide the definition of race and/or ethnicity used in the study?^‡^ | How does the article define race and/or ethnicity? | Does the article specifically report how race and/or ethnicity was measured? | How race and/or ethnicity was measured | Does the article describe how race and/or ethnicity was coded? | How race and/or ethnicity was coded
Alexander, 2010^72^ | Yes | No | NR | Yes | Response to questionnaire administered by researcher | Yes | African American (other races/ethnicities not identified in paper)
Asiodu, 2015^73^ | Yes | No | NR | Yes | Self-identification | Yes | African American
Asiodu, 2017^74^ | Yes | No | NR | Yes | Self-identification | Yes | African American
Avery, 2009^75^ | Yes | No | NR | Yes | Self-identification | Yes | African American, Caucasian
Ayers, 2022^76^ | Yes | No | NR | Yes | Self-identification | Yes | Marshallese
Bader, 2020^77^ | Yes | No | NR | No | NR | Yes | Burundian, Congolese (of African origin)
Barbosa, 2017^78^ | Yes | No | NR | No | NR | Yes | non-Hispanic/Latina African American
Bartick, 2012^79^ | Yes | No | NR | Yes | Self-identification | Yes | Latina (Dominican, Ecuadoran, Mexican, Puerto Rican, Hispanic)
Biediger-Friedman, 2016^80^ | No | No | NR | No | NR | Yes | Black, Hispanic, Other, White
Bookhart, 2021^81^ | Yes | No | NR | No | NR | Yes | Asian or Asian American, Black, Other, White; Hispanic, Non-Hispanic
Carlin, 2019^82^ | No | No | NR | Yes | Self-identification | Yes | African American, Caucasian
Chopel, 2019^83^ | No | No | NR | No | NR | Yes | African American or Black, Asian, Hispanic or Latino
Cottrell, 2013^84^ | Yes | No | NR | Yes | Self-identification | Yes | African American
Davis, 2021^85^ | Yes | No | NR | Yes | Self-identification | Yes | Black (Non-Hispanic)
Deubel, 2019^86^ | Yes | No | NR | Yes | Self-identification | Yes | African American
DeVane-Johnson, 2018^87^ | Yes | No | NR | Yes | Self-identification | Yes | African American
Fabiyi, 2016^88^ | Yes | No | NR | No | NR | Yes | Black (African American and African-born)
Felder, 2022^89^ | Yes | No | NR | Yes | Self-identification | Yes | African American
Fischer, 2014^90^ | Yes | No | NR | Yes | Self-identification | Yes | African American, White
Furman, 2013^91^ | Yes | No | NR | No | NR | Yes | Non-Hispanic African American
Glassman, 2014^92^ | Yes | No | NR | YES | Questionnaire | Yes | African American, Latino/a, Other, White
Gross, 2017^95^ | Yes | No | NR | Yes | Self-identification | Yes | African American
Gross, 2019^94^ | Yes | No | NR | Yes | Self-identification | Yes | Hispanic and/or Latina
Gross, 2022^93^ | Yes | No | NR | No | NR | Yes | Hispanic/Latinx
Haughton, 2010^96^ | No | No | NR | Yes | Survey | Yes | African American, Other, Puerto Rican, West Indian/Jamaican, White/Caucasian
Henshaw, 2018^97^ | Yes | No | NR | Yes | Online screening form | Yes | African American, Hispanic, White
Hill, 2012^98^ | Yes | No | NR | No | NR | Yes | Somali
Hinson, 2018^99^ | Yes | No | NR | No | NR | Yes | African American
Hohl, 2016^100^ | Yes | No | NR | Yes | Self-identification | Yes | Hispanic/Latina
Jefferson, 2021^101^ | Yes | No | NR | Yes | Self-identification | Yes | African American
Jefferson, 2022^102^ | Yes | No | NR | Yes | Self-identification | Yes | African American
Johnson, 2015^103^ | Yes | No | NR | Yes | Self-identification | Yes | African American
Johnson, 2016^104^ | Yes | No | NR | Yes | Self-identification | Yes | African American/Black
Joshi, 2014^105^ | Yes | No | NR | No | NR | Yes | Hispanic
Kadakia, 2015^106^ | Yes | No | NR | Yes | Self-identification | Yes | African American
Kaufman, 2010^107^ | Yes | No | NR | No | NR | Yes | African American, Puerto Rican
Kim, 2017^108^ | Yes | No | NR | Yes | Self-report | Yes | African American, Black, Mixed Ethnicity
Lebron, 2021^110^ | Yes | No | NR | Yes | Self-identification | Yes | Hispanic
Lee, 2015^111^ | Yes | No | NR | No | NR | Yes | Chinese American
Lee, 2018^112^ | Yes | No | NR | No | NR | Yes | Korean
Lee, 2021^113^ | Yes | No | NR | Yes | Self-identification | Yes | Black/African-American
Lewallen, 2010^114^ | Yes | No | NR | Yes | Self-identification | Yes | African American
Lindsay, 2017^115^ | Yes | No | NR | No | NR | Yes | Brazilian
Lutenbacher, 2016^116^ | Yes | No | NR | Yes | Self-identification | Yes | Black
Ma, 2018^117^ | Yes | No | NR | Yes | Self-identification | Yes | Latina or Hispanic
McGlothen, 2018^118^ | No | No | NR | Yes | Questionnaire | Yes | Hispanic (other races/ethnicities not identified in paper)
Munn, 2018^119^ | Yes | No | NR | No | NR | Yes | African American
Muse, 2021^120^ | Yes | No | NR | No | NR | Yes | African American
Obeng, 2014^122^ | Yes | No | NR | No | NR | Yes | Black
Obeng, 2015^121^ | Yes | No | NR | No | NR | Yes | African American
Owens, 2018^123^ | Yes | No | NR | Yes | Self-identification | Yes | African American
Peacock-Chambers, 2017^124^ | Yes | No | NR | NR | NR | Yes | Hispanic, Other, White (non-Hispanic)
Pearlman Shapiro, 2022^125^ | No | No | NR | Yes | Interview | Yes | Asian, Black, Latinx, White
Racine, 2009^126^ | No | No | NR | No | NR | Yes | African American, Asian, Caucasian
Ringel Kulka, 2011^109^ | Yes | No | NR | Yes | Self-identification | Yes | African American
Robinson, 2009^128^ | Yes | No | NR | No | NR | Yes | African American
Robinson, 2011^130^ | Yes | No | NR | No | NR | Yes | African American
Robinson, 2016^129^ | Yes | No | NR | No | NR | Yes | African American
Robinson, 2019^127^ | Yes | No | NR | Yes | Self-identification | Yes | African American
Schindler-Ruwisch, 2019^132^ | Yes | No | NR | No | NR | Yes | African American
Schindler-Ruwisch, 2020^131^ | Yes | No | NR | No | NR | Yes | African American
Shipp, 2021^133^ | Yes | No | NR | Yes | Self-identification | Yes | African American
Sloand, 2018^134^ | Yes | No | NR | Yes | Self-identification | Yes | Latina
Spencer, 2015^135^ | Yes | No | NR | Yes | Self-identification | Yes | African American
Steinman, 2010^136^ | Yes | Yes | Social construct | No | NR | Yes | Somali
Teich, 2014^137^ | No | No | NR | No | NR | Yes | Asian/Non-Hispanic, Bi-/Multiracial/Other, Black/Non-Hispanic, Hispanic, White
Textor, 2013^138^ | Yes | No | NR | No | NR | Yes | Mexican, Somali
Tucker, 2011^139^ | Yes | No | NR | No | NR | Yes | Black, Hispanic, White
Vaughn, 2010^140^ | Yes | No | NR | No | NR | Yes | Latina
Wambach, 2016^141^ | Yes | No | NR | No | NR | Yes | Mexican American
Woods Barr, 2021^142^ | Yes | No | NR | No | NR | Yes | African American
Woods Barr, 2021^143^ | Yes | No | NR | Yes | Self-identification | Yes | African American

* Abbreviations: NR, not reported

† Questions used to assess how race and ethnicity were examined adapted from: Martinez RAM, Andrabi N, Goodwin AN, Wilbur RE, Smith NR, Zivich PN. Resource Packet for “Clear communication of race and ethnicity for public health: best practices & common failings”. 2021. doi: 10.17615/dcfj-9g46

‡ e.g., social construct, biological construct

Table A-7 How race and ethnicity were examined in included articles (Key Question 3)^*^,^†^

Study | Does the article describe why race and/or ethnicity was important to the research question? | Does the article provide the definition of race and/or ethnicity used in the study?^‡^ | Does the article specifically report how race and/or ethnicity was measured? | How race and/or ethnicity was measured | Does the article describe how race and/or ethnicity was coded? | How race and/or ethnicity was coded
Ahlers-Schmidt, 2020^179^ | Yes | No | Yes | Birth certificate | Yes | Non-Hispanic White, Non-Hispanic Black, Hispanic, Other
Ahluwalia, 2012^180^ | Yes | No | Yes | Self-reported | Yes | Black, Hispanic, Other, White
Beauregard, 2022^181^ | Yes | No | No (but notes that survey instruments are available publicly) | NR | Yes | Hispanic, Non-Hispanic Black or African American, Non-Hispanic White, Other
Bonuck, 2014^182^ | Yes | No | Yes | Interview | Yes | Biracial/multiracial/oth er, Hispanic, Non-Hispanic Asian, Non-Hispanic Black, Non-Hispanic White
Burnham, 2022^183^ | Yes | No | Yes | Birth certificate (reported by parent) or medical record (reported by parents or hospital staff) | Yes | Black (Non-Hispanic), Other, White (Non-Hispanic), Hispanic
Caine, 2012^151^ | Yes | No | Yes | Medical records | Yes | White (non-Hispanic), Black (non-Hispanic), Hispanic, Other
Campbell, 2014^152^ | No | No | No | NR | Yes | White, Black, Hispanic, Asian, Native American, Other
Chae, 2017^184^ | No | No | No | NR | Yes | Asian, African American, Latina, White, Other
Chapman, 2013^185^ | No | No | Yes | Interview | Yes | Hispanic, African American, White, Other
Chiasson, 2013^178^ | No | No | Yes | Administrative records | Yes | Asian, Black Non-Hispanic, Hispanic, Other, White Non-Hispanic
Cloutier, 2018^153^ | Yes | No | Yes | Self-report via questionnaire | Yes | African American/Black, Hispanic, Other, Unknown
Dennison, 2022^226^ | Yes | No | Yes | Abstracted from NY State Expanded Birth Certificate | Yes | Hispanic, Non-Hispanic Black, Non-Hispanic Other, Non-Hispanic White
Disantis, 2010^186^ | No | No | Yes | Clinic interview | Yes | African American, Hispanic; (other races/ethnicities not reported)
Edmunds, 2017^154^ | No | No | Yes | Self-reported at WIC certification | Yes | Non-Hispanic Black, Non-Hispanic White, Non-Hispanic Other, Hispanic
Edwards, 2013^187^ | Yes | No | No | NR | Yes | African American
Efrat, 2015^188^ | Yes | No | Yes | Self-identification | Yes | Hispanic
Ekambaram, 2019^189^ | Yes | No | Yes | Extracted from electronic medical record | Yes | African American, Caucasian, Hispanic, Other
Gabbe, 2017^155^ | Yes | No | No | NR | Yes | African American/Non-Hispanic Black
Gleason, 2020^156^ | No | No | Yes | Interview | Yes | Non-Hispanic Black, Non-Hispanic White, Non-Hispanic Other, Hispanic
Grassley, 2011^190^ | No | No | Yes | Self-report | Yes | African American, Hispanic/Latina, Mixed/Other, White
Griffin, 2021^145^ | Yes | No | Yes | Self-report via survey | Yes | White, Black, Hispanic, Asian, Other
Gross, 2011^158^ | No | No | Yes | WIC certification interview | Yes | Non-Hispanic African American, Non-Hispanic White, Hispanic, Non-Hispanic Other (Asian, Native American, Other)
Gross, 2009^157^ | No | No | Yes | WIC certification interview | Yes | Non-Hispanic White, Non-Hispanic African American, Non-Hispanic Other (Asian Americans, Native Americans, Pacific Islanders), Hispanic, Unknown Race
Gross, 2016^191^ | No | No | Yes | Self-identification | Yes | Hispanic/Latina
Gruber, 2013^192^ | Yes | No | No | NR | Yes | African American, Other, White
Gurtcheff, 2011^146^ | No | No | No | NR | Yes | Other, White, White Hispanic
Hamad, 2019^227^ | No | No | Yes | Self-report via telephone survey | Yes | Black, Hispanic, Other, White
Hans, 2018^193^ | Yes | No | Yes | Self-identification | Yes | Black/African American, Latina/Hispanic, White, Multiracial/Other
Harari, 2018^159^ | Yes | No | Yes | Report via intake form | Yes | Black, Hispanic (Puerto-Rican or not), White, Other
Harris-Luna, 2018^160^ | Yes | No | No | NR | Yes | Hispanic
Hawkins, 2013^228^ | Yes | No | Yes | Self-report via survey | Yes | Black, Hispanic, Other, White
Hemingway, 2021 | Yes | No | Yes | Collected from medical record | Yes | Black Non-Hispanic, Hispanic, Other Ethnicity/Race, White Non-Hispanic; For analyses dichotomized Black vs Non-Black
Hopkinson, 2009^195^ | Yes | No | No | NR | Yes | Hispanic (Born in USA, Mexico, El Salvador, Honduras, or Guatemala)
Howell, 2014^196^ | Yes | No | Yes | Self-identification | Yes | Black/African American, Hispanic/Latina
Jenkins, 2020^161^ | No | No | Yes | Self-report | Yes | Asian, Black American, Black Other, Caucasian, Hispanic, Indian, Other
Jung, 2019^197^ | No | No | Yes | Self-report via phone interview | Yes | Hispanic (vs not)
Kao, 2015^198^ | No | No | No | NR | Yes | African American, Caucasian, Hispanic, Other
Kapinos, 2017^234^ | Yes | No | Yes | Birth certificate | Yes | American Indian/Alaska Native, Asian/Pacific Islander, Black, White; Hispanic
Keenan-Devlin, 2021^199^ | Yes | No | Yes | Medical record | Yes | White, Black, Other, Asian, Latinx
Kelly, 2017^200^ | Yes | No | Yes | Self-report via survey | Yes | African American, Latino, Other, White
Kettrey, 2020^201^ | Yes | No | Yes | Medical record | Yes | Black/African American, Hispanic, White
Klima, 2009^202^ | Yes | No | No | NR | Yes | African American
Knutson, 2022^203^ | Yes | No | No | NR | Yes | Asian, Hispanic, Non-Hispanic Black, Non-Hispanic White
Kozhimannil, 2013^204^ | Yes | No | Yes | Self-report | Yes | White, African American, African descent (African-born black), Hispanic, Asian, Native American, Other
Langellier, 2012^205^ | Yes | No | Yes | Phone interview | Yes | Hispanic, Non-Hispanic Black, Non-Hispanic White, Other/Multi
Langellier, 2014^229^ | Yes | No | Yes | Self-report via phone interview | Yes | Asian, Black, Latina, Other or Multiple, White
Lau, 2021^206^ | Yes | No | Yes | Self-identification | Yes | Chinese American
Lewkowitz, 2018^162^ | Yes | No | Yes | Self-identification | Yes | African American
Lewkowitz, 2020^147^ | Yes | No | Yes | Self-report via survey | Yes | White, Black, Hispanic, Asian, Other
Lewkowitz, 2021^148^ | No | No | Yes | Self-report via survey | Yes | White, Black, Hispanic, Asian, Other
Li, 2019^163^ | No | No | Yes | Self-identification via survey | Yes | Non-Hispanic Black, Mexican American, Other Hispanic, Other Races, Non-Hispanic White
Linares, 2019^207^ | Yes | No | Yes | Self-identification | Yes | Hispanic
Little, 2021^144^ | No | No | No | NR | Yes | Latina (vs not)
Lovera, 2010^164^ | Yes | No | Yes | Self-report | Yes | Hispanic
Lutenbacher, 2022^165^ | Yes | No | Yes | Self-identification | Yes | Hispanic
Lutenbacher, 2018^166^ | Yes | No | Yes | Self-identification | Yes | Nation of origin: Costa Rica, El Salvador, Guatemala, Honduras, Mexico, Peru
Martinez, 2020^208^ | Yes | No | Yes | Self-report via survey | Yes | Non-Hispanic White, Non-Hispanic Black, White Hispanic, Black Hispanic, Asian, Other
Martinez-Brockman, 2018a^168^ | No | No | No | NR | Yes | Hispanic, Non-Hispanic
Martinez-Brockman, 2018b^167^ | No | No | Yes | Self-identification | Yes | Hispanic, Non-Hispanic
Merewood, 2019^209^ | Yes | No | Yes | Birth certificate (reported by parent) or medical record (reported by parents or hospital staff) | Yes | African American Non-Hispanic, Hispanic, Other, White Non-Hispanic
Mersky, 2021^169^ | Yes | No | Yes | Self-identification | Yes | Hispanic, African American/Black, Other
Moon, 2017^210^ | Yes | No | Yes | Self-identification | Yes | African American
Nobari, 2017^211^ | No | No | Yes | Self-report via phone interview | Yes | Hispanic (vs not)
Nommsen-Rivers, 2009^212^ | No | No | Yes | In-person interview | Yes | African American, Asian, Hispanic, White Non-Hispanic
Palacios, 2018^149^ | Yes | No | No | No | Yes | American Indian, Asian, Black, Hispanic, Native Hawaiian, Pacific Islander, White
Patberg, 2021^213^ | Yes | No | Yes | Self-identification | Yes | Black, White
Petrova, 2009^214^ | No | No | No | NR | Yes | White, Black, Hispanic, Asian
Pezley, 2022^150^ | Yes | No | Yes | Self-identification | Yes | Black, African American; Hispanic, Non-Hispanic
Pitcock, 2021^215^ | Yes | No | No | NR | Yes | Hispanic
Pugh, 2010^216^ | No | No | Yes | Self-report | Yes | African American, White, Latina, Other
Qureshey, 2020^217^ | No | No | Yes | Medical records | Yes | African American/Black, Hispanic
Reat, 2015^230^ | No | No | Yes | Telephone survey | Yes | Hispanic, Non-Hispanic White, Other (Asian and blended races)
Reeder, 2014^170^ | No | No | No | NR | Yes | White and Non-Hispanic, White and Hispanic, Native American and Hispanic, All Other Races and Ethnicities
Reifsnider, 2018^171^ | Yes | No | No | NR | Yes | Latina
Robertson, 2009^218^ | Yes | No | Yes | Self-identification | Yes | Hispanic
Rosen-Carole, 2022^219^ | No | No | Yes | Self-identification via participant interview | Yes | Black or African American; White/Caucasian; Hispanic or Latina; Asian or Pacific or Alaska Native; Other
Rotheram-Fuller, 2017a^173^ | Yes | No | No | NR | Yes | Korean, Latina
Rotheram-Fuller, 2017b^172^ | Yes | No | No | NR | Yes | Korean, Latina
Sandy, 2009^174^ | Yes | No | Yes | Self-report | Yes | Latina (Dominican, Puerto Rican, Mexican, Salvadoran, Other Latin American countries, African American or African)
Schreck, 2017^220^ | Yes | No | Yes | Medical records | Yes | Black/African American, White, Other
Scott, 2019^221^ | Yes | No | Yes | Medical records | Yes | Marshallese
Sebastian, 2019^222^ | Yes | No | Yes | Self-report via survey | Yes | English-speaking Hispanic, Non-Hispanic Native American, Other, Spanish-speaking Hispanic, White non-Hispanic
Smith-Gagen, 2014a^231^ | No | No | Yes | Self-identification via survey | Yes | Black, Mexican, Other, White
Smith-Gagen, 2014b^232^ | Yes | No | Yes | Self-report via survey with discrete choices | Yes | African American, Mexican American, White
Stuebe, 2016^223^ | No | No | No | NR | Yes | American Indian/Alaskan Native, Asian, Black/African American, White, More than one race, Other; Hispanic, Not Hispanic
Tussing-Humphreys, 2019^175^ | Yes | No | Yes | Self-report | Yes | African American, White
Ventura, 2022^176^ | No | No | Yes | Self-report via questionnaire | Yes | Hispanic
Washio, 2017^177^ | Yes | No | Yes | Self-identification | Yes | Puerto Rican
Watt, 2015^224^ | Yes | No | Yes | Self-report via survey | Yes | Hispanic
Wilde, 2012^233^ | No | No | Yes | Administrative records | Yes | Hispanic, Non-Hispanic Black, Other, Non-Hispanic White
Wilhelm, 2015^225^ | Yes | No | Yes | Self-identification | Yes | Mexican-American

* Abbreviations: NR, not reported; vs, versus; WIC, Special Supplemental Nutrition Program for Women, Infants, and Children

† Questions used to assess how race and ethnicity were examined adapted from: Martinez RAM, Andrabi N, Goodwin AN, Wilbur RE, Smith NR, Zivich PN. Resource Packet for “Clear communication of race and ethnicity for public health: best practices & common failings”. 2021. doi: 10.17615/dcfj-9g46

‡ e.g., social construct, biological construct