# Appendix 2 Literature search strategy

## Database: PubMed

Provider: U.S. National Library of Medicine

Date(s) Searched: June 22,2022

Table A-2 PubMed electronic database search and results

Search # | Concept | String | Results
#1 | Human milk feeding | “Breast Feeding”[Mesh] OR “breast fe*”[tiab] OR “breastfe*”[tiab] OR “Milk, Human”[Mesh] OR “breast milk”[tiab] OR “breastmilk”[tiab] OR “human milk”[tiab] OR “mother’s milk”[tiab] OR “mothers’ milk”[tiab] OR “mother’s own milk”[tiab] OR “mothers’ own milk”[tiab] OR “maternal milk”[tiab] OR “milk fe*”[tiab] OR “Bottle Feeding”[Mesh] OR “bottle fe*”[tiab] | 88,231
#2 | Race and/or ethnicity | “Racial Groups”[MeSH] OR “Ethnicity”[MESH] OR Race[tiab] OR racial*[tiab] OR racism[tiab] OR ethnic*[tiab] OR cultur*[tiab] OR African American*[tiab] OR American Indian*[tiab] OR Native American*[tiab] OR Alaska Native*[tiab] OR Native Alaskan*[tiab] OR Hawaiian Native*[tiab] OR Native Hawaiian*[tiab] OR indigenous[tiab] OR Pacific Islander*[tiab] OR Asian*[tiab] OR black[tiab] OR blacks[tiab] OR Hispanic*[tiab] OR Latina*[tiab] OR Latino*[tiab] OR Latinx[tiab] OR white[tiab] OR whites[tiab] OR multiethnic[tiab] OR multiracial[tiab] OR sociodemographic*[tiab] OR socio demographic*[tiab] OR underserved[tiab] OR under-served[tiab] OR underrepresented[tiab] OR under-represented[tiab] | 2,283,019
#3 | Socioeconomic status | “Socioeconomic Factors”[Mesh] OR “Food Assistance”[Mesh] OR “Poverty”[Mesh] OR low income[tiab] OR socioeconomic[tiab] OR socio economic[tiab] OR poverty[tiab] OR Financ*[tiab] OR Supplemental Nutrition Assistance Program[tiab] OR SNAP[tiab] OR Women Infants and Children Program[tiab] OR WIC[tiab] OR temporary assistance for needy families[tiab] OR TANF[tiab] OR Special Supplemental Nutrition Program for Women Infants and Children [tiab] OR welfare[tiab] OR Medicaid[tiab] OR Public assistance[tiab] OR food assistance[tiab] | 782,727
#4 | Interventions | “Health Education”[Mesh] OR Intervention*[tiab] OR Counsel*[tiab] OR education*[tiab] OR encourag*[tiab] OR support*[tiab] OR baby friendly[tiab] OR facilitat*[tiab] OR promot*[tiab] OR policy[tiab] OR policies[tiab] OR program[tiab] OR problem*[tiab] OR barrier*[tiab] OR maternity leave[tiab] OR parental leave[tiab] OR “Parental Leave”[Mesh] | 6,487,862
#5 | Disparities | Healthcare Disparities[MeSH] OR Health equity[MeSH] OR Health Status disparities[MeSH] OR Social Determinants of Health[MeSH] OR Determinants of Health[tiab] OR disparit*[tiab] OR factors[tiab] OR difference*[tiab] OR equal*[tiab] OR inequalit*[tiab] OR bias*[tiab] OR inequit*[tiab] OR gap[tiab] OR gaps[tiab] OR stereotype*[tiab] OR equity[tiab] | 5,629,316
#6 | | #1 AND (#2 OR #3) AND (#4 OR #5) | 12,928
#7 | | #6 NOT (“Animals”[Mesh] NOT (“Animals”[Mesh] AND “Humans”[Mesh])); NOT (editorial[ptyp] OR comment[ptyp] OR commentary[tiab] OR news[ptyp] OR letter[ptyp] OR review[ptyp] OR systematic review[ptyp] OR systematic review[ti] OR meta-analysis[ptyp] OR meta-analysis[ti] OR meta-analyses[ti] OR protocol[ti] OR protocols[ti] OR retracted publication[ptyp] OR retraction of publication[ptyp] OR retraction of publication[tiab] OR retraction notice[ti] OR “retracted publication”[ti] OR “Congress”[Publication Type] OR “Consensus Development Conference”[Publication Type] OR “conference abstract*”[tiab] OR “conference proceeding*”[tiab] OR “conference paper*”[tiab] OR “practice guideline”[ptyp] OR “practice guideline”[ti]); Filters: from 2009 – 2022, English | 6,471

## Database: CINAHL

Provider: EBSCO

Date(s) Searched: June 22, 2022

Table A-3 CINAHL electronic database search and results

Search # | Concept | String | Results
#1 | Human milk feeding | (MH ‘Bottle Feeding’) OR (MH ‘Breast Feeding+’) OR (MH ‘Milk, Human+’) OR (TI ‘breast fe*’ OR ‘breastfe*’ OR ‘breast milk’ OR ‘breastmilk’ OR ‘human milk’ OR ‘mother’s milk’ OR ‘mothers’ milk’ OR ‘mother’s own milk’ OR ‘mothers’ own milk’ OR ‘maternal milk’ OR ‘bottle fe*’) OR (AB ‘breast fe*’ OR ‘breastfe*’ OR ‘breast milk’ OR ‘breastmilk’ OR ‘human milk’ OR ‘mother’s milk’ OR ‘mothers’ milk’ OR ‘mother’s own milk’ OR ‘mothers’ own milk’ OR ‘maternal milk’ OR “milk fe*” OR ‘bottle fe*’) | 40,995
#2 | Race and/or ethnicity | (MH “Race Factors”) OR (MH “Minority Groups”) OR (MH “Race Relations+”) OR (MH “Ethnic Groups+”) OR (MH “Hispanic Americans+”) OR (TI Race OR racial* OR racism OR ethnic* OR cultur* OR African American* OR American Indian* OR Native American* OR Alaska Native* OR Native Alaskan* OR Hawaiian Native* OR Native Hawaiian* OR indigenous OR Pacific Islander* OR Asian* OR black OR blacks OR Hispanic* OR Latina* OR Latino* OR Latinx OR white OR whites OR multiethnic OR multiracial OR sociodemographic* OR “socio demographic*” OR underserved OR “under-served” OR underrepresented OR “under-represented”) OR (AB Race OR racial* OR racism OR ethnic* OR cultur* OR African American* OR American Indian* OR Native American* OR Alaska Native* OR Native Alaskan* OR Hawaiian Native* OR Native Hawaiian* OR indigenous OR Pacific Islander* OR Asian* OR black OR blacks OR Hispanic* OR Latina* OR Latino* OR Latinx OR white OR whites OR multiethnic OR multiracial OR sociodemographic* OR “socio demographic*” OR underserved OR “under-served” OR underrepresented OR “under-represented”) | 630,845
#3 | Socioeconomic status | (MH “Socioeconomic Factors+”) OR (MH “Food Assistance”) OR (MH “Poverty”) OR (TI “low income” OR socioeconomic OR “socio economic” OR poverty OR Financ* OR “Supplemental Nutrition Assistance Program” OR SNAP OR “Women Infants and Children Program” OR WIC OR “temporary assistance for needy families” OR TANF OR “Special Supplemental Nutrition Program for Women Infants and Children” OR welfare OR Medicaid OR “Public assistance” OR “food assistance”) OR (AB “low income” OR socioeconomic OR “socio economic” OR poverty OR Financ* OR “Supplemental Nutrition Assistance Program” OR SNAP OR “Women Infants and Children Program” OR WIC OR “temporary assistance for needy families” OR TANF OR “Special Supplemental Nutrition Program for Women Infants and Children” OR welfare OR Medicaid OR “Public assistance” OR “food assistance”) | 607,002
#4 | Interventions | (MH “Health Education+”) OR (MH “Peer Counseling”) OR (MH “Counseling”) OR (MH “Parental Leave”) OR (MH “Hospital Policies+”) OR (MH “Public Policy+”) OR (TI Intervention* OR Counsel* OR education* OR encourag* OR support* OR “baby friendly” OR facilitat* OR promot* OR policy OR policies OR program OR problem* OR barrier* OR “maternity leave” OR “parental leave”) OR (AB Intervention* OR Counsel* OR education* OR encourag* OR support* OR “baby friendly” OR facilitat* OR promot* OR policy OR policies OR program OR problem* OR barrier* OR “maternity leave” OR “parental leave”) | 2,507,861
#5 | Disparities | (MH “Healthcare Disparities”) OR (MH “Health Status Disparities”) OR (MH “Social Determinants of Health”) OR (TI “Determinants of Health” OR disparit* OR factors OR difference* OR equal* OR inequalit* OR bias* OR inequit* OR gap OR gaps OR stereotype* OR equity) OR (AB “Determinants of Health” OR disparit* OR factors OR difference* OR equal* OR inequalit* OR bias* OR inequit* OR gap OR gaps OR stereotype* OR equity) | 2,296,510
#6 | | #1 AND (#2 OR #3) AND (#4 OR #5) | 8,792
#7 | | #6 NOT ((MH “Animals+”) OR (MH “Animal Studies”)); NOT ((MH “Literature Review”) OR (MH “Meta Analysis”) OR (MH “Systematic Review”) OR (MH “News”) OR (MH “Retracted Publication”) OR (MH “Retraction of Publication) OR (MH “Congresses and Conferences”)); English, Apply equivalent subjects, Published Date: 20090101-20221231 | 6,121

## Database: Web of Science Core Collection

Provider: Clarivate

Date(s) Searched: June 22, 2022

Table A-4 Web of Science electronic database search and results

Search # | Concept | String | Results
#1 | Human milk feeding | TS=(“breast feed*” OR “breast fed” OR “breastfe*” OR “human milk” OR “breast milk” OR “breastmilk” OR “human milk” OR “mother’s milk” OR “mothers’ milk” OR “mother’s own milk” OR “mothers’ own milk” OR “maternal milk” OR “milk feed*” OR “milk fed” OR “bottle feed”* OR “bottle fed”) | 69,532
#2 | Race and/or ethnicity | TS=(Race OR racial* OR racism OR ethnic* OR cultur* OR “African American*” OR “American Indian*” OR “Native American*” OR “Alaska Native*” OR “Native Alaskan*” OR “Hawaiian Native*” OR “Native Hawaiian*” OR “Pacific Islander*” OR Asian* OR black OR blacks OR Hispanic OR Latina* OR Latino* OR Latinx OR white OR whites OR multiethnic OR multiracial OR sociodemographic* OR “socio demographic*” OR underserved OR “under-served” OR underrepresented OR “under-represented”) | 3,181,952
#3 | Socioeconomic status | TS=(“low income” OR socioeconomic OR “socio economic” OR poverty OR Financ* OR “Supplemental Nutrition Assistance Program” OR SNAP OR “Women Infants and Children Program” OR WIC OR “temporary assistance for needy families” OR TANF OR “Special Supplemental Nutrition Program for Women Infants and Children” OR welfare OR Medicaid OR “Public assistance” OR “food assistance”) | 789,021
#4 | Interventions | TS=(Intervention* OR Counsel* OR education* OR encourag* OR support* OR “baby friendly” OR facilitat* OR promot* OR policy OR policies OR program OR problem* OR barrier* OR “maternity leave” OR “parental leave”) | 10,870,258
#5 | Disparities | TS=(“Determinants of Health” OR disparit* OR factors OR difference* OR equal* OR inequalit* OR bias* OR inequit* OR gap OR gaps OR stereotype* OR equity) | 10,488,242
#6 | | #1 AND (#2 OR #3) AND (#4 OR #5) | 8,166
#7 | | #6 NOT DT=(Book OR Book Chapter OR Book Review OR Correction OR Correction, Addition OR Editorial Material OR Meeting Abstract OR Meeting Summary OR Proceedings Paper OR Review); Publication Date: 2009-01-01 to 2022-12-31 | 5,344