# Appendix 1 Abbreviations

Table A-1 List of abbreviations
Abbreviation: Full name
AMSTAR 2: A MeaSurement Tool to Assess systematic Reviews 2
BINGO: Best Infant Nutrition of Good Outcomes study
BMI: Body mass index
CDC: Centers for Disease Control and Prevention
CHAMPS: Communities and Hospitals Advancing Maternity Practices Study
CNPP: Center for Nutrition Policy and Promotion
ECLS-B: Early Childhood Longitudinal Study – Birth Cohort
FNS: Food and Nutrition Service
IFPS: Infant Feeding Practices Survey
ITFPS-2: Infant and Toddler Feeding Practices Study 2
KQ: Key question
LATCH: Lactation Advice thru Texting Can Help
NESR: Nutrition Evidence Systematic Review
NEST: Nutrition, Exercise, and coping Skills Training study
NGAD: Nutrition Guidance and Analysis Division
NHANES: National Health and Nutrition Examination Survey
NICU: Neonatal intensive care unit
NIMHD: National Institute of Minority Health and Health Disparities
NIS-Child: National Immunization Survey-Child
NRCT: Non-randomized controlled trial
NSCH: National Survey of Children’s Health
NSFG: National Survey of Family Growth
NVSS: National Vital Statistics System
OPS: Office of Policy Support
PAIRINGS: Provider Approaches to Improved Rates of Infant Nutrition and Growth Study
PCS: Prospective cohort study
PNSS: Pregnancy Nutritional Surveillance System
PRAMS: Pregnancy Risk Assessment Monitoring System
PSID: Panel Study of Income Dynamics
RCS: Retrospective cohort study
RCT: Randomized controlled trial
RoB 2.0: Version 2 of the Cochrane tool for assessing risk of bias in randomised trials
ROBINS-I: Risk Of Bias In Non-randomised Studies – of Interventions
RoB-NObs: Risk of Bias for Nutrition Observational Studies
SES: Socioeconomic status
SNAS-RAD: Supplemental Nutrition and Safety Research and Analysis Division
U.S.: United States
USDA: United States Department of Agriculture
WIC: Special Supplemental Nutrition Program for Women, Infants, and Children