# ACKNOWLEDGEMENTS

Frequency of Eating Subcommittee:

- Steven Heymsfield, MD, Louisiana State University, Pennington Biomedical Research Center, Subcommittee Chair
- Carol Boushey, PhD, MPH, RD, University of Hawaii
- Heather Leidy, PhD, University of Texas at Austin
- Richard Mattes, PhD, MPH, RD, Purdue University
- Ronald Kleinman, MD, Massachusetts General Hospital, Harvard Medical School, Vice-Chair of the 2020 Dietary Guidelines Advisory Committee

Nutrition Evidence Systematic Review (NESR) Team:

- Emily Callahan, MS, Analyst, Nutrition Guidance and Analysis Division (NGAD), Center for Nutrition Policy and Promotion (CNPP), Food and Nutrition Service (FNS), U.S. Department of Agriculture (USDA)
- Gisela Butera, MLIS, MEd, Systematic Review Librarian, Panum Group.^i^
- Nancy Terry, MLS, Biomedical Librarian, National Institutes of Health (NIH) Library, U.S. Department of Health and Human Services (HHS)
- Julie Obbagy, PhD, RD, Project Lead, NGAD, CNPP, FNS, USDA

Federal Liaisons:

- Ashley Vargas, PhD, MPH, RDN, FAND, Eunice Kennedy Shriver National Institute of Child Health and Human Development, NIH, HHS
- Meghan Adler, MS, RD, FAND, NGAD, CNPP, FNS, USDA
- Rebecca MacIsaac, MS, RD, Division of Prevention Science (DPS), Office of Disease Prevention and Health Promotion (ODPHP), Office of the Assistant Secretary for Health (OASH), HHS
- Julia Quam, MSPH, RDN, DPS, ODPHP, OASH, HHS

Project Leadership:

- Eve Stoody, PhD, Designated Federal Officer and Director, NGAD, CNPP, FNS, USDA
- Janet de Jesus, MS, RD, Nutrition Advisor, ODPHP, OASH, HHS
- Colette Rihane, MS, RD, Director, NGAD, CNPP, FNS, USDA (through October 2019)

USDA and HHS implemented a process to identify topics and scientific questions to be examined by the 2020 Dietary Guidelines Advisory Committee. The Committee conducted its review of evidence in subcommittees for discussion by the full Committee during its public meetings. The role of the Committee members involved establishing all aspects of the protocol, which presented the plan for how they would examine the scientific evidence, including the inclusion and exclusion criteria; reviewing all studies that met the criteria they set; deliberating on the body of evidence for each question; and writing and grading the conclusion statements to be included in the scientific report the 2020 Committee submitted to USDA and HHS. The NESR team with assistance from Federal Liaisons and Project Leadership, supported the Committee by facilitating, executing, and documenting the work necessary to ensure the reviews were completed in accordance with NESR methodology. More information about the 2020 Dietary Guidelines Advisory Committee, including the process used to identify topics and questions, can be found at www.DietaryGuidelines.gov. More information about NESR can be found at NESR.usda.gov.

i Under contract with the Food and Nutrition Service, United States Department of Agriculture.