# List of abbreviations

Abbreviation: Full name
CNPP: Center for Nutrition Policy and Promotion
DPS: Division of Prevention Science
FoE: Frequency of eating
FNS: Food and Nutrition Service
HHS: Health and Human Services
NESR: Nutrition Evidence Systematic Review
NIH: National Institute of Health
ONGA: Office of Nutrition Guidance and Analysis
USDA: United States Department of Agriculture