# METHODOLOGY

The NESR team used its rigorous, protocol-driven methodology to support the 2020 Dietary Guidelines Advisory Committee in conducting this systematic review.

NESR’s systematic review methodology involves:

- Developing a protocol,
- Searching for and selecting studies,
- Extracting data from and assessing the risk of bias of each included study,
- Synthesizing the evidence,
- Developing conclusion statements,
- Grading the evidence underlying the conclusion statements, and
- Recommending future research.

A detailed description of the methodology used in conducting this systematic review is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews, and can be found in the 2020 Dietary Guidelines Advisory Committee Report, Part C: Methodology.^ii^ Additional information about this systematic review, including a description of and rationale for any modifications made to the protocol can be found in the 2020 Dietary Guidelines Advisory Committee Report, Chapter 13. Frequency of Eating.

Below are details of the final protocol for the systematic review described herein, including the:

- Analytic framework
- Literature search and screening plan
- Literature search and screening results

## ANALYTIC FRAMEWORK

The analytic framework (Figure 1) illustrates the overall scope of the systematic review, including the population, the interventions and/or exposures, comparators, and outcomes of interest. It also includes definitions of key terms and identifies key confounders considered in the systematic review. The inclusion and exclusion criteria that follow provide additional information about how parts of the analytic framework were defined and operationalized for the review.

Figure 1 Analytic framework

An analytic framework visually represents the overall scope of the systematic review question, and depicts the contributing elements that were examined and evaluated, including the target population, exposure, comparison, outcomes, and key confounders. This is the analytic framework for the systematic review question on the relationship between the frequency of eating and all-cause mortality. For this systematic review, the target population considered was children and adolescents (ages 2-18 years old), adults (ages 19-64 years old), women during pregnancy or lactation, and older adults (ages 65 and older) who were healthy and/or at risk of chronic disease. The interventions or exposures considered were frequency of eating, or the number of daily eating occasions. The outcomes considered were all-cause mortality. The key confounders being considered were sex, age, race/ethnicity, habitual eating frequency, smoking, and anthropometry. The other factors to be considered were: socioeconomic status, physical activity, cultural practices, total energy intake, diet energy density, energy state of the diet (restriction/surplus), energy balance (total energy intake/total energy expenditure), chrononutrition factors (time of day, (consistency of) habitual eating frequency, and duration between ingestive events and/or ingestive periods), portion size, macronutrient content, location of eating occasion, habitual eating frequency, eating environment (who you eat with, work/school/exercise schedule), holiday eating (seasonal), sleep schedule (shift work), secondary eating, dentition, hydration status, pregnancy status, pubertal status, menopausal status, and biochemical changes.

## LITERATURE SEARCH AND SCREENING PLAN

### Inclusion and exclusion criteria

This table provides the inclusion and exclusion criteria for the systematic review. The inclusion and exclusion criteria are the set of characteristics used to determine which articles identified in the literature search were included in or excluded from the systematic review.

Table 1 Inclusion and exclusion criteria

Category | Inclusion Criteria | Exclusion Criteria
Study design | - Randomized controlled trials; - Non-randomized controlled trials, including quasi-experimental and controlled before and after studies; - Prospective cohort studies; - Retrospective cohort studies; - Nested case-control studies | - Uncontrolled trials; - Case-control studies; - Cross-sectional studies; - Uncontrolled before-and-after studies; - Narrative reviews; - Systematic reviews; - Meta-analyses
Intervention/exposure | Frequency of eating:; - Number of daily eating occasions | - Studies that only examine frequency of intake of a single food, beverage or category of foods or beverages (i.e. frequency of milk consumption, frequency of seafood consumption); - Studies that do not have eating occasions across the day
Comparator | - Different number of daily eating occasions | - N/A
Outcomes | - Studies that report all-cause mortality (i.e., total mortality): the total number of deaths from all causes during a specific time-period. | - Studies that only report cause-specific mortality (total number of deaths from a specific disease, such as cardiovascular disease or cancer)
Date of publication | - January 2000 – June 2019 | - Articles published prior to or after January 2000 – June 2019
Publication status | - Articles published in peer-reviewed journals | - Articles that have not been peer-reviewed and are not published in peer-reviewed journals (e.g. unpublished data, manuscripts, reports, abstracts, pre-prints, and conference proceedings)
Language of publication | - Articles published in English | - Articles published in languages other than English
Country ^iii^ | - Studies conducted in countries ranked as high or very high human development | - Studies conducted in countries ranked as medium or lower human development
Study participants | - Human participants; - Males; - Females; - Females during pregnancy and the post-partum period | ○ Non-human participants (i.e., animals or in-vitro models)
Health status of study participants | - Studies that enroll participants who are healthy and/or at risk for chronic disease, including those with obesity; - Studies that enroll some participants diagnosed with a disease | - Studies that exclusively enroll participants diagnosed with a disease (for this criterion, studies that exclusively enroll subjects with obesity will be included); - Studies that exclusively enroll subjects post bariatric surgery
Eating frequency data collection for intervention studies | - Data collection for eating frequency that occurs on at least 2 occasions, including baseline and during or after the intervention.; ○ Each occasion encompasses a minimum of 3, 24-hour periods or a questionnaire that covers at least 3 days addressing eating frequency.; ■ (e.g., 3, 24-h dietary recalls reporting ingestive events); ■ (e.g., 1 eating frequency questionnaire documenting eating frequency for the past month) | - Data collection for eating frequency that occurs on fewer than 2 occasions, and encompasses fewer than 3, 24-hour periods
Eating frequency data collection for observational studies | - Data collection for eating frequency that encompasses a minimum of 3, 24-hour periods; ○ (e.g., 3, 24-h dietary recalls reporting each ingestive event); ○ (e.g., 1 eating frequency questionnaire documenting eating frequency for the past month) | - Data collection for eating frequency that encompasses fewer than 3, 24-hour periods
Size of study groups for intervention studies | - 15 or greater participants for studies using within-subject analyses, or; - 30 or greater participants for studies using between-subject analysis, or; - A power calculation included | - Fewer than 15 participants for studies using within-subject analyses, or; - Fewer than 30 participants for studies using between-subject analysis, or; - No power calculation reported

### Electronic databases and search terms

#### PubMed

- Provider: U.S. National Library of Medicine
- Date(s) searched: June 19, 2019
- Date range searched: January 1, 2000-June 19, 2019
- Search Terms:
  - #1 - “frequency of eating” OR “eating frequency” OR “feeding frequency” OR “meals per day” OR beverage intake[tiab] OR “Meals”[Mesh] OR “meal frequency” OR “meal timing” OR “meal time” OR mealtime* OR daily meal* OR dinnertime* OR eating occasion* OR “snack frequency” OR “snacking frequency” OR “Fasting”[Mesh] OR “intermittent fasting” OR fasting diet* OR “alternate-day fasting” OR “meal skipping” OR “breakfast skipping” OR skipping breakfast* OR “drinking frequency” OR “infrequent consumption” OR “frequent consumption” OR “Feeding Behavior”[Mesh] OR feeding behavior*[tiab] OR eating pattern* OR time restricted feeding* OR meal profile* OR meal pattern* OR chrono-nutrition OR intermittent energy restriction* OR eating time*
  - #2 - “Mortality”[Mesh] OR “mortality” [Subheading] OR mortality [tiab]
  - #3 - (#1 AND #2)
  - #4 - (#1 AND #2) NOT (“Animals”[Mesh] NOT (“Animals”[Mesh] AND “Humans”[Mesh])) NOT (editorial[ptyp] OR comment[ptyp] OR news[ptyp] OR letter[ptyp] OR review[ptyp] OR systematic review[ptyp] OR systematic review[ti] OR meta-analysis[ptyp] OR meta-analysis[ti] OR meta-analyses[ti] OR retracted publication[ptyp] OR retraction of publication[ptyp] OR retraction of publication[tiab] OR retraction notice[ti]) Filters: Publication date from 2000/01/01 to 2019/06/19; English

#### Cochrane Central Register of Controlled Trials (CENTRAL)

- Provider: John Wiley & Sons
- Date(s) searched: June 19, 2019
- Date range searched: January 1, 2000-June 19, 2019
- Search Terms:
  - #1 - [mh Meals] OR [mh Fasting] OR [mh “Feeding Behavior”]
  - #2 - (“frequency of eating” OR “eating frequency” OR “feeding frequency” OR “meals per day” OR “beverage intake” OR “meal frequency” OR “meal timing” OR “meal time” OR mealtime* OR daily meal* OR dinnertime* OR “eating occasion*” OR “snack frequency” OR “snacking frequency” OR “intermittent fasting” OR “fasting diet*” OR “alternate-day fasting” OR “meal skipping” OR “breakfast skipping” OR “skipping breakfast*” OR “drinking frequency” OR “infrequent consumption” OR “frequent consumption” OR “Feeding Behavior”[Mesh:NoExp] OR “feeding behavior*” OR “eating pattern*” OR “time restricted feeding*” OR “meal profile*” OR “meal pattern*” OR chrono-nutrition OR “intermittent energy restriction*” OR “eating time*”):ti,ab,kw
  - #3 - #1 OR #2
  - #4 - [mh Mortality] OR [mh /MO]
  - #5 - (mortality):ti,ab,kw
  - #6 - #4 OR #5
  - #7 - #3 AND #6” with Publication Year from 2000 to 2019, in Trials (Word variations have been searched)

#### Embase

- Provider: Elsevier
- Date(s) searched: June 19, 2019
- Date range searched: January 1, 2000-June 19, 2019
- Search Terms:
  - #1 - ‘frequency of eating’:ab,ti OR ‘eating frequency’:ab,ti OR ‘feeding frequency’:ab,ti OR ‘meals per day’:ab,ti OR ‘beverage intake’:ab,ti OR ‘meal frequency’:ab,ti OR ‘meal timing’:ab,ti OR ‘meal time’:ab,ti OR mealtime*:ab,ti OR ‘daily meal*’:ab,ti OR dinnertime*:ab,ti OR ‘eating occasion*’:ab,ti OR ‘snack frequency’:ab,ti OR ‘snacking frequency’:ab,ti OR ‘intermittent fasting’:ab,ti OR ‘fasting diet*’:ab,ti OR ‘alternate-day fasting’:ab,ti OR ‘meal skipping’:ab,ti OR ‘breakfast skipping’:ab,ti OR ‘skipping breakfast*’:ab,ti OR ‘drinking frequency’:ab,ti OR ‘infrequent consumption’:ab,ti OR ‘frequent consumption’:ab,ti OR ‘feeding behavior*’:ab,ti OR ‘eating pattern*’:ab,ti OR ‘time restricted feeding*’:ab,ti OR ‘meal profile*’:ab,ti OR ‘meal pattern*’:ab,ti OR ‘chrono nutrition’:ab,ti OR ‘intermittent energy restriction*’:ab,ti OR ‘eating time*’:ab,ti
  - #2 - ‘meal’/exp OR ‘fasting’/exp OR ‘feeding behavior’/exp
  - #3 - #1 OR #2
  - #4 - ‘mortality’/exp
  - #5 - mortality:ab,ti
  - #6 - #4 OR #5
  - #7 - #3 AND #6 AND ([article]/lim OR [article in press]/lim) AND [humans]/lim AND [english]/lim AND [2000-2019]/py NOT ([conference abstract]/lim OR [conference review]/lim OR [conference paper]/lim OR [editorial]/lim OR [erratum]/lim OR [letter]/lim OR [note]/lim OR [review]/lim OR [systematic review]/lim OR [meta analysis]/lim)

## LITERATURE SEARCH AND SCREENING RESULTS

The flow chart (Figure 2) below illustrates the literature search and screening results for articles examining the systematic review question. The results of the electronic database searches, after removal of duplicates, were screened independently by two NESR analysts using a step-wise process by reviewing titles, abstracts, and full-texts to determine which articles met the inclusion criteria. Refer to Table 2 for the rationale for exclusion for each excluded full-text article. A manual search was done to find articles that were not identified when searching the electronic databases; all manually identified articles were also screened to determine whether they meet criteria for inclusion.

Figure 2 Flow chart of literature search and screening results

This flow chart illustrates the literature search and screening results for articles examining the relationship between thefrequency of eating and all-cause mortality. The literature search yielded 4,791 articles. After duplicates were removed, 4,174 articles were screened at the title level. During title screening, 4,030 articles were screened out. During abstract screening, 126 articles were screened out. During full-text screening, 18 articles were screened out. During the hand search, 0 additional articles were identified to include. A total of 0 articles were included in the systematic review at the end of the search and screening process.

### Excluded articles

The table below lists the articles excluded after full-text screening, and includes a column to document the rationale for study exclusion based on the criteria in Table 1. At least one reason for exclusion is provided for each article, though this may not reflect all possible reasons for exclusion. Information about articles excluded after title and abstract screening is available upon request.

Table 2 Articles excluded after full text screening with rationale for exclusion

| Citation | Rationale
1 | Rong, S, Snetselaar, LG, Xu, G, Sun, Y, Liu, B, Wallace, RB, Bao, W. Association of skipping breakfast with cardiovascular and all-cause mortality. J Am Coll Cardiol. 2019. 73:2025-2032. doi:10.1016/j.jacc.2019.01.065. | Eating Frequency Data Collection
2 | Al Assaad, RG, Bachir, R, El Sayed, MJ. Impact of Ramadan on emergency department visits and on medical emergencies. Eur J Emerg Med. 2018. 25:440-444. doi:10.1097/mej.0000000000000485. | Intervention/ Exposure
3 | Pruimboom, L, Muskiet, FAJ. Intermittent living; the use of ancient challenges as a vaccine against the deleterious effects of modern life - A hypothesis. Med Hypotheses. 2018. 120:28-42. doi:10.1016/j.mehy.2018.08.002. | Study Design
4 | Elbarsha, A, Elhemri, M, Lawgaly, SA, Rajab, A, Almoghrabi, B, Elmehdawia, RR. Outcomes and hospital admission patterns in patients with diabetes during Ramadan versus a non-fasting period. Ann Saudi Med. 2018. 38:344-351. doi:10.5144/0256-4947.2018.344. | Health Status
5 | Cummings, JR, Mason, AE, Puterman, E, Tomiyama, AJ. Comfort eating and all-cause mortality in the US Health and Retirement Study. Int J Behav Med. 2018. 25:473-478. doi:10.1007/s12529-017-9706-8. | Intervention/ Exposure
6 | Loprinzi, PD, Addoh, O, Mann, JR. Association between dietary behavior and mortality among American adults with mobility limitations. Disabil Health J. 2018. 11:126-129. doi:10.1016/j.dhjo.2017.05.006. | Intervention/ Exposure
7 | Lengyel, CO, Jiang, D, Tate, RB. Trajectories of nutritional risk: The Manitoba Follow-Up Study. J Nutr Health Aging. 2017. 21:604-609. doi:10.1007/s12603-016-0826-7. | Intervention/ Exposure, Outcome
8 | Chen, HJ, Wang, Y, Cheskin, LJ. Relationship between frequency of eating and cardiovascular disease mortality in U.S. adults: the NHANES III follow-up study. Ann Epidemiol. 2016. 26:527-533. doi:10.1016/j.annepidem.2016.06.006. | Eating Frequency Data Collection
9 | Dai, J, Krasnow, RE, Reed, T. Midlife moderation-quantified healthy diet and 40-year mortality risk from CHD: the prospective National Heart, Lung, and Blood Institute Twin Study. Br J Nutr. 2016. 116:326-34. doi:10.1017/s0007114516001914. | Intervention/ Exposure
10 | Menotti, A, Puddu, PE, Maiani, G, Catasta, G. Cardiovascular and other causes of death as a function of lifestyle habits in a quasi extinct middle-aged male population. A 50-year follow-up study. Int J Cardiol. 2016. 210:173-8. doi:10.1016/j.ijcard.2016.02.115. | Intervention/ Exposure
11 | Yokoyama, Y, Onishi, K, Hosoda, T, Amano, H, Otani, S, Kurozawa, Y, Tamakoshi, A. Skipping breakfast and risk of mortality from cancer, circulatory diseases and all causes: findings from the Japan Collaborative Cohort Study. Yonago Acta Med. 2016. 59:55-60. | Eating Frequency Data Collection
12 | Zhou, T, Li, X, Tang, Z, Xie, C, Tao, L, Pan, L, Huo, D, Sun, F, Luo, Y, Wang, W, Yan, A, Guo, X. Risk factors of CVD mortality among the elderly in Beijing, 1992 - 2009: an 18-year cohort study. Int J Environ Res Public Health. 2014. 11:2193-208. doi:10.3390/ijerph110202193. | Intervention/ Exposure
13 | Capewell, S, O’Flaherty, M. Rapid mortality falls after risk-factor changes in populations. Lancet. 2011. 378:752-3. doi:10.1016/s0140-6736(10)62302-1. | Study Design
14 | Bener, A, Hamad, A, Fares, A, Al-Sayed, HM, Al-Suwaidi, J. Is there any effect of Ramadan fasting on stroke incidence?. Singapore Med J. 2006. 47:404-8. | Outcome, Health Status
15 | Velten, APC, Cade, NV, Silva, GAE, Oliveira, ERA. Profile of mortality from external causes among Seventh-day Adventists and the general populations. Ciencia & saude coletiva. 2017. 22:2375-2382. doi:10.1590/1413-81232017227.13792015. | Intervention/ Exposure
16 | Beck, AM. Weight loss, mortality and associated potentially modifiable nutritional risk factors among nursing home residents — A Danish follow-up study. Journal of Nutrition, Health and Aging. 2014. 19:96-101. doi:10.1007/s12603-015-0439-6. | Intervention/ Exposure
17 | Giles, GG, English, DR. The Melbourne Collaborative Cohort Study. IARC scientific publications. 2002. 156:69-70. | Study Design, Intervention/ Exposure
18 | Lopez-Legarrea, P, De la Iglesia, R, Abete, I, Ibanez-Melo, A, Navas-Carretero, S, Bondia-Pons, I, Forga, L, Zulet, M, Martinez, A. The Resmena diet: a new effective dietary strategy for reducing metabolic syndrome. Obesity facts. 2012. 5:230-231. doi:10.1159/000258190. | Study Design, Publication Status

ii Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

iii In order to determine the inclusion exclusion criteria for country, the Human Development classification was used. This classification is based on the Human Development Index (HDI) ranking from the year the study intervention occurred or data were collected (UN Development Program. HDI 1990-2017 HDRO calculations based on data from UNDESA (2017a), UNESCO Institute for Statistics (2018), United Nations Statistics Division (2018b), World Bank (2018b), Barro and Lee (2016) and IMF (2018). Available from: http://hdr.undp.org/en/data). If the study did not report the year in which the intervention occurred or data were collected, the HDI classification for the year of publication was applied. HDI values are available from 1980, and then from 1990 to present. If a study was conducted prior to 1990, the HDI classification from 1990 was applied. If a study was conducted in 2018 or 2019, the most current HDI classification was applied. When a country was not included in the HDI ranking, the current country classification from the World Bank was used instead (The World Bank. World Bank country and lending groups. Available from: https://datahelpdesk.worldbank.org/knowledgebase/articles/906519-world-country-and-lending-groups)