# WHAT IS THE RELATIONSHIP BETWEEN THE FREQUENCY OF EATING AND ALL-CAUSE MORTALITY?

## PLAIN LANGUAGE SUMMARY

### What is the question?

- The question is: What is the relationship between the frequency of eating and all-cause mortality?

### What is the answer to the question?

- No evidence is available to determine the relationship between the frequency of eating and all-cause mortality

### Why was this question asked?

- This important public health question was identified by the U.S. Departments of Agriculture (USDA) and Health and Human Services (HHS) to be examined by the 2020 Dietary Guidelines Advisory Committee.

### How was this question answered?

- The 2020 Dietary Guidelines Advisory Committee, Frequency of Eating Subcommittee conducted a systematic review to answer this question with support from the Nutrition Evidence Systematic Review (NESR) team.
- Frequency of eating was defined as the number of daily eating occasions.

### What is the population of interest?

- The population of interest was generally healthy children through older adults (ages 2 and older).

### What evidence was found?

- This review identified 0 studies that met the inclusion criteria.

### How up-to-date is this systematic review?

- This review searched for studies from January, 2000 to June, 2019.

## FULL REVIEW

### Systematic review question

What is the relationship between the frequency of eating and all-cause mortality?

### Conclusion statement and grade

No evidence is available to determine the relationship between the frequency of eating and all-cause mortality. (Grade: Grade not assignable)

### Summary of the evidence

- This systematic review was undertaken to examine the relationship between the frequency of eating and all-cause mortality.
- All-cause mortality was defined as the total number of deaths from all causes during a specific time-period.
- This review identified 0 studies published between January, 2000 and June, 2019 that met the inclusion criteria for this systematic review.

### Research recommendations

- More controlled trials are needed that assess the frequency of eating and various outcomes.
- Future studies should develop a consistent definition of an ingestive event that includes eating and drinking and methods to quantify it.
- Future studies should document the frequency of water consumption.
- In future studies, collection of ingestive frequency data should:
  ○ Report number of ingestive events across 24 hours.
  ○ Collect a minimum of 3 days of ingestive event data on at least 2 discrete occasions to allow assessment of estimate reliability.
- Future studies should report information on food insecurity in relation to frequency of eating to allow isolation of voluntary versus involuntary eating frequency effects.
- Future research should report key confounders and other factors to be considered, such as:
  ○ Sex, Age, Race/ethnicity, Habitual eating frequency, Smoking, Anthropometry, Socioeconomic status, Physical activity, Cultural practices, Total energy intake, Diet energy density, Energy state of the diet (restriction/surplus), Energy balance (total energy intake/total energy expenditure), Chrononutrition factors (time of day, (consistency of) habitual eating frequency, and duration between ingestive events and/or ingestive periods), Portion size, Macronutrient content, Location of eating occasion, Eating environment (who you eat with, work/school/exercise schedule), Holiday eating (seasonal), Sleep schedule (shift work), Secondary eating, Dentition, Hydration status, Pregnancy status, Pubertal status, Menopausal status, Biochemical changes