# List of abbreviations

Abbreviation: Full name
BMI: Body mass index
FNS: Food and Nutrition Service
HHS: Health and Human Services
NESR: Nutrition Evidence Systematic Review
NIH: National Institute of Health
ODPHP: Office of Disease Prevention and Health Promotion
ONGA: Office of Nutrition Guidance and Analysis
USDA: United States Department of Agriculture