# WHAT IS THE RELATIONSHIP BETWEEN THE FREQUENCY OF EATING DURING LACTATION AND POSTPARTUM WEIGHT LOSS?

## PLAIN LANGUAGE SUMMARY

### What is the question?

- The question is: What is the relationship between the frequency of eating during lactation and postpartum weight loss?

### What is the answer to the question?

- Insufficient evidence is available to determine the relationship between the frequency of eating during lactation and postpartum weight loss.

### Why was this question asked?

- This important public health question was identified by the U.S. Departments of Agriculture (USDA) and Health and Human Services (HHS) to be examined by the 2020 Dietary Guidelines Advisory Committee.

### How was this question answered?

- The 2020 Dietary Guidelines Advisory Committee, Frequency of Eating Subcommittee conducted a systematic review to answer this question with support from the Nutrition Evidence Systematic Review (NESR) team.
- Frequency of eating was defined as the number of daily eating occasions.
- Postpartum weight loss was defined as a change in weight from baseline (postpartum) to a later time point during the postpartum period.

### What is the population of interest?

- The population of interest was women during lactation who were healthy and/or at risk of chronic disease.

### What evidence was found?

- This review included 1 prospective cohort study that met the inclusion criteria for this systematic review.
- The 1 included study did not report a significant association between a change in eating frequency and a change in weight from baseline over a 12-week follow-up.
- The study had several limitations.

### How up-to-date is this systematic review?

- This review searched for studies from January, 2000 to September, 2019.

## FULL REVIEW

### Systematic review question

What is the relationship between the frequency of eating during lactation and postpartum weight loss?

### Conclusion statement and grade

Insufficient evidence is available to determine the relationship between the frequency of eating during lactation and postpartum weight loss. (Grade: Grade not assignable)

### Summary of the evidence

- Frequency of eating was defined as the number of daily eating occasions. An eating occasion was defined as an ingestive event (solid food or beverage, including water) that is either energy yielding or non-energy yielding.
- Postpartum weight loss was defined as a change in weight from baseline (postpartum) to a later time point during the postpartum period. Additionally, it could be postpartum weight retention, if gestational weight gain was controlled for in the analysis.
- This review included 1 prospective cohort study (using data from a multicomponent randomized controlled trial) that met the inclusion criteria for this systematic review and was published within the date range of January 2000 and September 2019.
- The 1 included study did not report a significant association between a change in eating frequency and a change in weight from baseline over a 12-week follow-up.
- The study had several limitations, including:
  ○ Key confounders were not accounted for.
  ○ Data were from a multi-component randomized controlled trial that was not designed to test frequency of eating.
  ○ One prospective cohort study with critical limitations was not sufficient to draw conclusions.

### Description of the evidence

This systematic review included 1 article that addressed the relationship between the frequency of eating during lactation and postpartum weight loss, published between January 2000 and September 2019.^1^ Basic characteristics of the study are shown in Table 1. The study was a prospective cohort study that used data from a randomized controlled trial, the Lifestyle for Effective Weight Loss during Lactation (LEVA) trial, and was conducted in Sweden. The original intent of the multi-component randomized controlled trial was to investigate a diet and exercise behavior modification program on body weight and body composition in a population of overweight and obese lactating women. One component of the intervention was to reduce the number of eating occasions.

Huseinovic et al^1^ examined the change in eating frequency per a decrease in 1 eating occasion between baseline and 12-week follow-up in relation to change in weight during the same time period.

Participants were a small sample of women (n=60) who were 10-14 weeks postpartum at baseline and 22-26 weeks postpartum at follow-up. Mean age of the women was 33 years, and all were either overweight or had obesity at baseline (mean BMI was 30kg/m^2^). The average parity was 1; 95% of participants were exclusively breastfeeding; and 5% were partially breastfeeding. Average habitual eating frequency at baseline was about 6 eating occasions per day.

### Evidence synthesis

In Huseinovic et al^1^ a change in eating frequency was not significantly associated with a change in postpartum weight over a 12-week follow-up. Results are shown in Table 1. Eating frequency was assessed using a 4-day weighed dietary record and an eating occasion was defined as an energy intake (food or beverage) of ≥50 kcal, separated in time from the preceding and following eating occasion by at least 30 minutes. Water consumption was not considered in the analysis.

There were many limitations within the included study (Table 2). Key confounders, such as smoking and gestational weight gain were not accounted for in the analysis. The data used for this analysis were secondary, and eating frequency was not the sole focus of the randomized controlled trial from which the data were derived. The trial was multi-component in nature, and therefore a number of co-interventions that were intended to also impact postpartum weight were not accounted for in the analysis. Additionally, there was no assessment of participants’ dietary intake (i.e., composition or quality).

The results from this one study were insufficient to draw a conclusion about the relationship between the frequency of eating during lactation and postpartum weight loss.

### Research recommendations

- More controlled trials are needed that assess the frequency of eating and various outcomes.
- Future studies should develop a consistent definition of an ingestive event that includes eating and drinking and methods to quantify it.
- Future studies should document the frequency of water consumption.
- In future studies, collection of ingestive frequency data should:
  ○ Report number of ingestive events across 24 hours.
  ○ Collect a minimum of 3 days of ingestive event data on at least 2 discrete occasions to allow assessment of estimate reliability.
- Future studies should report information on food insecurity in relation to frequency of eating to allow isolation of voluntary versus involuntary eating frequency effects.
- Future research should report key confounders and other factors to be considered, such as:
  ○ Sex, Age, Race/ethnicity, Habitual eating frequency, Smoking, Anthropometry
  ○ Socioeconomic status, Physical activity, Cultural practices, Total energy intake, Diet energy density, Energy state of the diet (restriction/surplus), Energy balance (total energy intake/total energy expenditure), Chrononutrition factors (time of day, (consistency of) habitual eating frequency, and duration between ingestive events and/or ingestive periods), Portion size, Macronutrient content, Location of eating occasion, Eating environment (who you eat with, work/school/exercise schedule), Holiday eating (seasonal), Sleep schedule (shift work), Secondary eating, Dentition, Hydration status, Pregnancy status, Pubertal status, Menopausal status, Biochemical changes

### Included articles

1 Huseinovic E, Winkvist A, Bertz F, Berteus Forslund H, Brekke HK. Eating frequency, energy intake and body weight during a successful weight loss trial in overweight and obese postpartum women. Eur J Clin Nutr. 2014;68(1):71–76.doi: 10.1038/ejcn.2013.200.24193227

Table 1 Description of the study on relationship between the frequency of eating during lactation and postpartum weight loss^ii^

Study and population characteristics | Intervention/Exposure, Comparator and Outcome(s) | Results | Key Confounders and Study Limitations
Huseinovic, 2014 ^1^; Prospective Cohort Study (using data from a Randomized Controlled Trial, the LEVA study), Sweden; Analytic N=60; Participant characteristics:; - Age: 33.2, SE=4.1; - Sex: 100% female; - Race/Ethnicity: NR; - Habitual eating frequency: ~6 EOs/d, range 4-10; - Smoking: NR; - Anthropometry: BMI ~30 kg/m^2^ (100% overweight or obese prepregnancy); weight ~86 kg; WC ~96 cm; - SES: 72% >3y past high school; - Breastfeeding: 95% exclusive, 4.9% partial; - Parity: 1; - Marital status: 95% married or cohabitating; Excluded from study or analysis: Prepregnancy BMI <25 or >35 kg/m^2^, not intending to breastfeed for 6mo, use of metabolism-affecting drug, missing diet records | Exposure of interest: Change in eating frequency per a decrease in 1 EO between baseline (when women were 10-14wk postpartum) and a 12wk f/u (at 22-26wk postpartum); [underlined: Assessment method and timing]: 4d weighed food record at baseline and 12 wks; an EO was defined as an energy intake of ≥50 kcal, including foods and/or beverages, separated in time from the preceding and following EO by at least 30 min; [underlined: Treatment of beverages:] Included if >50kcal; Outcomes and assessment methods:; Weight, height were collected at baseline and 12wk by study personnel | Decrease in eating frequency (−1 EO) and change in postpartum weight from baseline to 12 wks: β = 0.9±0.7 kg, R^2^=42.3%, p =0.179; Summary: Change in eating frequency was not associated with change in postpartum weight | Model Adjustments:; - Key confounders: age, change in physical activity, pre-pregnancy BMI, eating frequency at baseline, dietary treatment. (parity was accounted for); Total energy intake adjusted: Yes; Limitations:; - Race/ethnicity (study took place in Sweden), smoking, and gestational weight gain were not accounted for in the analysis; - FoE assessment method not validated; - Intervention included many health co-interventions that were not accounted for in the FoE analysis; - No assessment of composition or quality of diet; - Beverages ≤50 kcals were not accounted for in FoE assessment; Funding sources: Swedish Research Council, Swedish Council for Working Life and Social Research

Table 2 Risk of bias for the prospective cohort study examining the frequency of eating during lactation and postpartum weight loss^iii,iv^

| Confounding | Selection of participants | Classification of exposures | Departures from intended exposures | Missing data | Outcome measurement | Selection of the reported result
Huseinovic, 2014^1^ | Serious | Low | Serious | Serious | Low | Low | Moderate

ii Abbreviations: EO: eating occasion; f/u: follow-up; FoE: frequency of eating; LEVA: Lifestyle for Effective Weight Loss during Lactation Trial; NR: not reported; SE: standard error; SES: socioeconomic status

iii A detailed description of the methodology used for assessing risk of bias is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

iv Possible ratings of low, moderate, serious, critical, or no information determined using the “Risk of Bias for Nutrition Observational Studies” tool (RoB-NObs) ( Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC. )