# List of abbreviations

Abbreviation: Full name
AFI: Abdominal fat index
BMI: Body mass index
CNPP: Center for Nutrition Policy and Promotion
DPS: Division of Prevention Science
FNS: Food and Nutrition Service
FoE: Frequency of eating
HHS: United States Department of Health and Human Services
NESR: Nutrition Evidence Systematic Review
NIH: National Institutes of Health
NR: Not reported
NS: No significant
ODPHP: Office of Disease Prevention and Health Promotion
ONGA: Office of Nutrition Guidance and Analysis
PMAX: Preperitoneal fat
SD: Standard deviation
SE: Standard error
SES: Socioeconomic status
SMIN: Subcutaneous fat
TEI: Total energy intake
USDA: United States Department of Agriculture