# WHAT IS THE RELATIONSHIP BETWEEN THE FREQUENCY OF EATING AND GROWTH, SIZE, BODY COMPOSITION, AND RISK OF OVERWEIGHT AND OBESITY?

## PLAIN LANGUAGE SUMMARY

### What is the question?

- The question is: What is the relationship between the frequency of eating and growth, size, body composition, and risk of overweight and obesity?

### What is the answer to the question?

- Insufficient evidence is available to determine the relationship between the frequency of eating and growth, size, body composition, and risk of overweight and obesity.

### Why was this question asked?

- This important public health question was identified by the U.S. Departments of Agriculture (USDA) and Health and Human Services (HHS) to be examined by the 2020 Dietary Guidelines Advisory Committee.

### How was this question answered?

- The 2020 Dietary Guidelines Advisory Committee, Frequency of Eating Subcommittee conducted a systematic review to answer this question with support from the Nutrition Evidence Systematic Review (NESR) team.
- Frequency of eating was defined as the number of daily eating occasions.

### What is the population of interest?

- The population of interest was generally healthy children through older adults (ages 2 and older).

### What evidence was found?

- This review identified 6 articles that met the inclusion criteria
- Results from the included studies were inconsistent.
- Many critical limitations in study design and conduct were identified in the included studies.
- The 2020 Committee could not draw conclusions.

### How up-to-date is this systematic review?

- This review searched for studies from January, 2000 to September, 2019.

## FULL REVIEW

### Systematic review question

What is the relationship between the frequency of eating and growth, size, body composition, and risk of overweight and obesity?

### Conclusion statement and grade

Insufficient evidence is available to determine the relationship between the frequency of eating and growth, size, body composition, and risk of overweight and obesity. (Grade: Grade not assignable)

### Summary of the evidence

- Frequency of eating was defined as the number of daily eating occasions.
  ○ An eating occasion was defined as an ingestive event (solid food or beverage, including water) that is either energy yielding or non-energy yielding.
- This review included 6 studies published between January 2000 and September 2019 that met the inclusion criteria for this systematic review: one randomized controlled trial^1^ and 5 prospective cohort studies.^2–6^
- Four out of 6 included studies reported an association between frequency of eating and at least one growth, size, body composition, or overweight and obesity outcome. However, the studies were inconsistent in terms of how they defined and examined frequency of eating, the outcomes they examined, and their reported results.
- Several critical limitations were identified within the body of evidence:
  ○ Studies varied in intervention or exposure assessment methods.
  ○ Definitions of eating occasions and number of eating occasions in the comparison groups varied in every included study.
  ○ Outcomes varied across studies: BMI, change in BMI, body fat, fat-free mass, waist circumference, change in waist circumference, 5 kg weight gain, weight change, subcutaneous fat, preperitoneal fat, and abdominal fat index.
  ○ Eating frequency assessment was only conducted at baseline leading to concerns of possible changes over time.
  ○ Both energy yielding and non-energy yielding beverages were inconsistently accounted for within eating occasion definitions across studies.
  ○ Water consumption was not explicitly mentioned in any included study.
  ○ High or unknown attrition rates.
  ○ Study populations did not fully represent the race/ethnic or socioeconomic diversity of the American population.
- Due to the inconsistency and limitations in the body of evidence included in this systematic review, it was determined that the evidence was insufficient to draw conclusions about the relationship between frequency of eating and growth, size, body composition, and risk of overweight and obesity.

### Description of the evidence

This systematic review included 6 articles that examined the relationship between the frequency of eating and growth, size, body composition, and risk of overweight and obesity, published between January 2000 and September 2019.^1–6^ Detailed information about the studies is shown in Table 1. One study was a randomized controlled trial (RCT)^1^ and 5 were prospective cohort studies (PCS).^2–5^ Five of the studies were conducted in the United States^1–4,6^ and one was conducted in Greece.^5^

The RCT randomized participants (n=45) to either 3 eating occasions per day or to consume at least 100 kcal every 2-3 hours (about 6 eating occasions per day) for 6 months.^1^ Both groups also received a standard behavioral intervention for obesity. The population was about 58% female, 94% White, 98% non-Hispanic, and all were overweight or had obesity (mean BMI of ~35 kg/m^2^).

One PCS was conducted in 9-11 year olds who were followed for 10 years.^2^ Four of the PCS were conducted in adults from ~18 years old to 66 years old.^3–6^ Two studies included only females,^2,3^ one included only males.^4^ In the 4 PCS in adults, mean BMI was ~26 kg/m^2^ at baseline. In the PCS in children, mean BMI was ~18 kg/m^2^ at baseline. Only 2 studies reported race/ethnicity; one population was ~50% White^2^ and one was 73% non-Hispanic White.^6^

Habitual eating frequency reported at baseline ranged from an average of 3.4 to 5 eating occasions per day. Three studies used 3-day dietary records,^1,2,5^ and 3 studies used a FFQ and added a question to assess number of daily eating occasions.^3,4,6^ Definitions of eating occasions varied across studies. Both energy yielding and non-energy yielding beverages were inconsistently accounted for within eating occasion definitions across studies. Water consumption was not explicitly mentioned in any included study. The number of eating occasions in comparison groups used in analyses varied in every included study. The types and amounts of foods that were consumed at eating occasions were not consistently reported.

Growth, size, and body composition outcomes varied across studies. Study outcomes reported included BMI, change in BMI, body fat, fat-free mass, waist circumference, change in waist circumference, 5 kg weight gain, weight change, subcutaneous fat, preperitoneal fat, and abdominal fat index.

### Evidence synthesis

The RCT by Bachman et al^1^ did not report a significant effect on BMI, body fat, or fat-free mass of consuming 3 versus 6 eating occasions per day for 6 months. This study had critical limitations. There was a difference in energy intake in the groups at baseline that was not accounted for in the analysis. The overall sample size was small, with 45 participants (23 participants in 3 eating occasions per day, 22 participants in 6 eating occasions per day) completing the study. Further, all participants were overweight or had obesity and were ready to enter a weight loss intervention, which may make them less generalizable to the U.S. population. Finally, the study did not include non-energy yielding beverages as a meal or snack, and the treatment of water consumption was not described.

The 5 PCS included in this review reported mixed results (Table 1). Of the 4 studies conducted in adults, 3 studies reported a positive association between frequency of eating and growth, size, and body composition outcomes. In Mekary et al,^3^ greater frequency of eating in a cohort of women, age 66 years, was significantly associated with higher BMI after 6 years of follow-up. However, no confounders were accounted for or adjusted for in this analysis. In van der Heijden et al,^4^ authors reported that a greater number of eating occasions, in addition to 3 standard meals, was associated with a higher risk of a 5-kg weight gain over 10 years of follow-up in a cohort of men. The choice of a 5-kg difference in weight gain was arbitrary and was not comparable to the other included studies. Georgiopoulos et al^5^ reported contradictory findings. Lower eating frequency (having 5 or less eating occasions per day compared to 6 or more eating occasions) was significantly associated with an increased abdominal fat index after a 5-year follow-up. However, lower eating frequency was also associated with a decrease in preperitoneal fat, and had no association with BMI, waist circumference, or subcutaneous fat. LaRose et al^6^ did not report any significant associations between frequency of eating at baseline and weight change at 4 months or 2 years of follow-up. Many confounders, such as age, sex, race/ethnicity, and smoking, were not accounted for in the analysis, nor where important co-interventions, such as physical activity.

Ritchie et al^2^ analyzed data from a cohort of girls, 9-11 years old, and reported that greater frequency of eating at baseline was associated with lower BMI and smaller waist circumference after 10 years of follow-up.

In all included PCS, there were critical limitations (Tables 2 and 3). The majority of studies had very high or unknown attrition rates. While habitual eating frequency was assessed using a validated method (e.g., 3-day dietary record, or an FFQ with questions specific to number of daily eating occasions), it was only assessed once at baseline, leading to concerns that changes in exposure status could have occurred over the study follow-ups.

Furthermore, the definition of eating occasions was not consistent across included studies. Ritchie et al^2^ defined an eating occasion as any consumption of foods or beverages recorded at a single clock time, regardless of the amount or type of food or beverage. Mekary et al^3^ asked participants, “How many times per day do you eat?” and participants were asked to include meals and snacks but did not mention beverages. In van der Heijden et al,^4^ authors asked participants to indicate if they ate at different times of the day anchored by meals (before breakfast, breakfast, between breakfast and lunch, lunch, between lunch and dinner, dinner, between dinner and bedtime, or after going to bed). Georgiopoulos et al^5^ defined an eating occasion as when food or beverages were consumed at least 15 minutes apart. LaRose et al^6^ reported using an eating pattern questionnaire that assessed frequency over the past 30 days, but did not report the exact question or the definition of eating occasion used. Additionally, no included studies explicitly mentioned how they handled water consumption within their eating occasion definition. The differences in these methods made it difficult to compare results across studies.

The 6 studies included in this systematic review were designed to examine the relationship between frequency of eating and growth, size, body composition, and risk of overweight and obesity, and were generalizable to the U.S. population. However, they were inconsistent in how they defined and examined frequency of eating, the outcomes considered, and the reported results. In addition, the included studies had a number of critical risks of bias due to their design and conduct. Publication bias is a concern with this body of evidence given that there were few studies and results are mixed. Therefore, the evidence was insufficient to be able to draw conclusions about the relationship between the frequency of eating and growth, size, body composition, and risk of overweight and obesity.

### Research recommendations

- More controlled trials are needed that assess the frequency of eating and various outcomes.
- Future studies should develop a consistent definition of an ingestive event that includes eating and drinking and methods to quantify it.
- Future studies should document the frequency of water consumption.
- In future studies, collection of ingestive frequency data should:
  ○ Report number of ingestive events across 24 hours.
  ○ Collect a minimum of 3 days of ingestive event data on at least 2 discrete occasions to allow assessment of estimate reliability.
- Future studies should report information on food insecurity in relation to frequency of eating to allow isolation of voluntary versus involuntary eating frequency effects.
- Future research should report key confounders and other factors to be considered, such as:
  ○ Sex, Age, Race/ethnicity, Habitual eating frequency, Smoking, Anthropometry
  ○ Socioeconomic status, Physical activity, Cultural practices, Total energy intake, Diet energy density, Energy state of the diet (restriction/surplus), Energy balance (total energy intake/total energy expenditure), Chrononutrition factors (time of day, (consistency of) habitual eating frequency, and duration between ingestive events and/or ingestive periods), Portion size, Macronutrient content, Location of eating occasion, Eating environment (who you eat with, work/school/exercise schedule), Holiday eating (seasonal), Sleep schedule (shift work), Secondary eating, Dentition, Hydration status, Pregnancy status, Pubertal status, Menopausal status, Biochemical changes

### Included articles

1 Bachman JL, Raynor HA. Effects of manipulating eating frequency during a behavioral weight loss intervention: a pilot randomized controlled trial. Obesity. 2012;20(5):985–992.doi: 10.1038/oby.2011.360 22173575
2 Ritchie LD. Less frequent eating predicts greater BMI and waist circumference in female adolescents. Am J Clin Nutr. 2012;95(2):290–296.doi: 10.3945/ajcn.111.016881 22218154
3 Mekary RA, Giovannucci E, Cahill L, Willett WC, van Dam RM, Hu FB. Eating patterns and type 2 diabetes risk in older women: breakfast consumption and eating frequency. Am J Clin Nutr. 2013;98(2):436–443.doi: 10.3945/ajcn.112.057521 23761483
4 van der Heijden AA, Hu FB, Rimm EB, van Dam RM. A prospective study of breakfast consumption and weight gain among U.S. men. Obesity. 2007;15(10):2463–2469.doi: 10.1038/oby.2007.292.17925472
5 Georgiopoulos G, Karatzi K, Yannakoulia M, . Eating frequency predicts changes in regional body fat distribution in healthy adults. QJM. 2017;110(11):729–734.doi: 10.1093/qjmed/hcx120 29017004
6 LaRose JG, Neiberg RH, Evans EW, . Dietary outcomes within the study of novel approaches to weight gain prevention (SNAP) randomized controlled trial. Int J Behav Nutr Phys Act. 2019;16(1):14.doi: 10.1186/s12966-019-0771-z 30704533

Table 1 Description of studies included in a systematic review to examine the relationship between the frequency of eating and growth, size, body composition, and risk of overweight and obesity^ii^

Study and population characteristics | Intervention/Exposure, Comparator and Outcome(s) | Results | Key Confounders and Study Limitations
Bachman, 2012^1^; Randomized Controlled Trial, United States; Analytic N=45; Participant characteristics:; - Age: 51y, SE=9.9; - Sex: 58% female; - Race/Ethnicity: 94.1% White, 5.9% Black; 98% Non-Hispanic, 2% Hispanic; - Habitual eating frequency: ~4 eating bouts/d (~2.8 meals, 1.2 snacks); - Smoking: NR; - Anthropometry: BMI 35.5 kg/m^2^ (100% overweight or obese); - SES: 8% high school, 4% vocational school, 31% some college, 31% college graduate, 26% graduate school; - Marital status: 78% married; Excluded from study or analysis: Age <21 and >65 y; BMI <27 and >45 kg/m^2^; Heart condition; chest pain or loss of consciousness during activity, unable to walk 2 blocks, major psychological disease; diabetes; recent weight loss or in a weight loss program; moving outside the area; pregnant, lactating, <6mo postpartum, or planned to become pregnant; unwilling to complete study meetings or assessments | Intervention:; [underlined: Participants randomized to 2 groups for a 6 mo trial:]; 3 Meal Group: Instructions to eat 3 meals/d + standard behavioral intervention for obesity for 6mo (~3 eating bouts/d at 3 and 6mo, all 3 meals); Grazing Group: Instructions to “graze” by eating at least 100 kcal every 2-3hr + standard behavioral intervention for obesity for 6mo (~6 eating bouts/d at 3 and 6mo, 3 meals and 3 snacks); [underlined: Assessment method and timing]: Intake of meals, snacks, and number of total eating bouts (meals, snacks) were assessed by 3 day (2 weekdays, 1 weekend) dietary records at 0, 3, and 6 mo.; Participants defined meals and snacks were only counted if at least 25kcal were consumed; [underlined: Treatment of beverages:] Non-calorie beverages would not be included as a meal or snack.; Outcomes and assessment methods:; Height was collected at baseline and weight was collected at 0, 3, and 6 mo; Body composition (% body fat, fat-free mass) was assessed by bioelectrical impedance analysis, at 0, 3, and 6 mo | BMI (kg/m2), 3 Meal Group (n=23) vs. Grazing Group (n=22):; - 0 mo: 35.7 ± 4.9 vs. 36.3 ± 5.4, p=ns; - 3 mo: 31.5 ± 4.1 vs. 32.5 ± 5.1, p=ns; - 6 mo: 29.8 ± 4.4 vs. 31.3 ± 5.3, p=ns; - Both groups significant decreased BMI at 3, 6mo vs 0mo (p<0.001); Body fat (%), 3 Meal Group vs. Grazing Group:; - 0 mo: 41.3 ± 7.0 vs. 40.2 ± 8.5, p=ns; - 3 mo: 37.6 ± 10.5 vs. 35.7 ± 9.2, p=ns; - 6 mo: 32.3 ± 9.3 vs. 33.1 ± 10.2, p=ns; - Both groups significant decreased body fat at 3, 6mo vs 0mo (p<0.001); Fat-free mass (kg), 3 Meal Group vs. Grazing Group:; - 0 mo: 58.8 ± 12.9 vs. 60.8 ± 15.2, p=ns; - 3 mo: 56.7 ± 14.5 vs. 60.0 ± 14.5, p=ns; - 6 mo: 57.9 ± 14.2 vs. 58.8 ± 12.6, p=ns; - No significant change in fat-free mass in either group at 3, 6mo vs 0mo (p=ns); Summary: There were no significant differences in BMI, body fat, or fat-free mass after consuming 3 vs 6 meals/d for 6 months. | Model Adjustments: N/A; TEI adjusted: No (3 Meal Group: 1111 kcal at 3mo, 1217 kcal at 6mo; Grazing Group: 1280kcal at 3mo, 1314 kcal at 6mo; p<0.0001); Limitations:; - Participants, carers, and trial personnel were not blinded; - Small sample size/underpowered; - Participants were ready to enter a weight loss intervention; - Short term intervention; - Did not include water as an eating occasion.; - Did not adjust for energy intake; Funding sources: American Heart Association
Ritchie, 2012 ^2^; Prospective Cohort Study, National Heart, Lung, and Blood Institute Growth and Health Study, United States; Analytic N=2146; Participant characteristics:; - Age: 9-10y; - Sex: 100% female; - Race/Ethnicity: 49% white, 51% black; - Habitual eating frequency: 4.96 ± 2.01 EO/ d; 2.59 ± 0.47 meals/d; 2.37 ± 2.14 snacks/d; - Smoking: NR; - Anthropometry: 18.6 kg/m^2^ BMI; 65.2cm waist circumference; - SES: ~8.6y of parental education; - Physical activity: ~“Sometimes” physically active; ~4.41 hr/d television/ video viewing; - Energy intake: 479±118 kcal/eating occasion, 641±135 kcal/meal, 150±48 kcal/snack; Excluded from study or analysis: not age within 2wk of 9-10y, black or white, living with parents or guardians with racial concordance, and parent or guardian providing information on the demographic characteristics; not missing data on any control variables | Exposure of interest:; Frequency of EO: 1-3 (n=236), 3.1-4 (n=619), 4.1-6 (n=908), >6 (n=383) times per day; [underlined: Assessment method and timing]:; 3 d dietary record at years 1, 2 (9-11y), averaged; total number of EO (meals and snacks combined; comprised all foods and beverages recorded at a single clock time, regardless of the amount or type of food or beverage);; Definition of meals and snacks: EO comprising ≥15% of total calories, regardless of the time of day or composition of foods or beverages consumed. All other EOs were a snack.; [underlined: Treatment of beverages:] Included in EO; water consumption not mentioned; Outcomes and assessment methods:; BMI (height, weight), waist circumference: Measured by study personnel at baseline and 10y f/u | [underlined: Change in BMI (mean ± SE):]; - 1-3 times/d: 7.83 ± 0.37; - 3.1-4 times/d: 7.35 ± 0.26; - 4.1-6 times/d: 7.28 ± 0.24; - >6 times/d: 6.54 ± 0.30; - p-value = 0.013; [underlined: Change in waist circumference (mean ± SE):]; - 1-3 times/d: 12.49 ± 0.86; - 3.1-4 times/d: 11.93 ± 0.64; - 4.1-6 times/d: 11.62 ± 0.60; - >6 times/d: 10.26 ± 0.72; - p-value = 0.036; Summary: Lower eating frequency at age 9-11y is associated with greater increases in BMI and waist circumference after 10 y of f/u. | Model Adjustments:; - Key confounders: sex, age, race/ethnicity, physical activity, anthropometry; - Other factors to be considered: SES, total energy intake; - Other: dieting for weight loss; TEI adjusted: Yes; Limitations:; - Smoking was not accounted for, but was not likely to be large issue in this population; - FoE assessment method not validated; - Frequency of eating was only assessed at baseline leading to a concern that changes in exposure status could have occurred over 10 y f/u; - Potential co-exposures were not likely assessed over 10 year f/u; - Water was not mentioned in FoE assessment; - No assessment of composition or quality of diet; Funding sources: USDA, NIH
Mekary, 2013^3^; Prospective Cohort Study, Nurses’ Health Study, United States; Analytic N=46289; Participant characteristics:; - Age: ~66y, SE=7; - Sex: 100% female; - Race/Ethnicity: NR; - Habitual eating frequency: ~4 EOs/d; 77% breakfast consumers; - Smoking: 8% current smokers; - Anthropometry: BMI ~26kg/m^2^; - Physical activity: ~18 MET/-h/wk; - Total energy intake: ~1700 kcal/d; - Family Hx of diabetes: 23%; - Postmenopausal hormone users: ~42%; - Alcohol intake: ~6 g/d; Excluded from study or analysis: Not a registered nurse; males, age <30 or >55 y at baseline; did not complete the baseline FFQ, had implausible energy intakes (>3500 or <500 kcal/d), did not answer the meal-frequency questions, diagnosed with diabetes, cardiovascular disease, and cancer (except for nonmelanoma skin cancer) | Exposure of interest: Frequency of EOs: 1-2, 3, 4-5, >6 times per day; [underlined: Assessment method and timing]: FFQ, collected in 2002; indicate eating times/day using question, “How many times per day do you eat? Include meals and snacks.” (for snacks, including juice and non-diet soda, but excluding coffee and diet soda); [underlined: Treatment of beverages]: Excluded coffee and diet soda from assessment; water and other non-caloric beverages were not mentioned; Outcomes and assessment methods:; - BMI: Self-reported height, weight; every 2y for 6y; - Type 2 diabetes: Self-reported, confirmed using an additional questionnaire and the American Diabetes Association criteria; every 2y for 6y | [underlined: Obesity after 6y:]; - 1-2 times/d: 25.7 kg/m2; - 3 times/: 25.6 kg/m2; - 4-5 times/d: 26.4 kg/m2; - >6 times/d: 26.6 kg/m2; - P<0.05; Summary: Women with higher frequency of eating at age 66y was significantly associated with higher BMI after 6y f/u. | Model Adjustments for Obesity:; - Key confounders: None; - Other factors to be considered: None; - Other: None; TEI adjusted: Yes; Limitations:; - No confounders accounted for in obesity outcomes. Race/ethnicity not accounted for in T2D analyses; - FoE assessment method not validated; - FoE data only assessed at baseline with a 6y f/u leading to a concern that changes in exposure status occurred over f/u; - High attrition rate; - Water and beverages other than juice and non-diet soda were not assessed or accounted for in FoE assessment; Funding sources: NIH
Van der Heijden, 2007 ^4^; Prospective Cohort Study, Health Professionals Follow-up Study, United States; Analytic N=20064; Participant characteristics:; - Age: ~57y; - Sex: 0% female; - Race/Ethnicity: NR; - Habitual eating frequency, all subjects: ~3.4 meals/d; - Habitual eating frequency, breakfast non-consumers/consumers: meals/d: 2.6/3.6; lunch: 77.9%/93.9%; dinner: 93.7%/98.6%; dietary intake between meals: before breakfast: 3.9%/0.4%; btw breakfast and lunch: 21.9%/7.4%; btw lunch and dinner: 11.1%/12.3%; btw dinner and bedtime: 48.7% vs. 44.5%; - Smoking: current smokers ~5.8%; - Anthropometry: BMI: ~25.6kg/m^2^; - Physical activity: ~38.3 MET/-h/wk; any weight training: ~21.4; - Macronutrient content: alcohol ~10.3 g/d; carbohydrate 49.4% energy; protein 18.2% energy; total fat 30.9% energy; Excluded from study or analysis: No baseline FFQ, implausible energy intakes (>4200 or <800 kcal/d), >70 food items blank, or missing values for breakfast skipping or BMI, diagnosed with diabetes, cardiovascular disease, and cancer (except nonmelanoma skin cancer) | Exposure of interest:; Frequency of EOs: 3, 4, ≥5 times per day; Breakfast non-consumers and breakfast consumers (2.6 vs. 3.6 meals/d); [underlined: Assessment method and timing]: FFQ, collected in 1992; indicate eating before breakfast, breakfast, between breakfast and lunch, lunch, between lunch and dinner, dinner, between dinner and bedtime, or after going to bed (question focused on eating, so likely beverages were not considered); [underlined: Treatment of beverages:] Likely not included; Outcomes and assessment methods:; Obesity: self-reported weight; weight change from baseline (1992) and follow-up (2002) was calculated; substantial weight gain was defined as ≥5kg | [underlined: Frequency of EOs and 5 kg weight gain]:; - 3 meals per day: HR 1.00; - +1 EO/d (n=4545): HR 1.07, 95% CI: 1.02 to 1.14; - +≥2 EO/d (n=4545): HR 1.15, 95% CI: 1.06 to 1.25; [underlined: Breakfast non-consumers vs. consumers and 5 kg weight gain:]; All men:; - Breakfast non-consumers (n=1312): HR 1.00; - Breakfast consumers (n=4545): HR 0.87, 95% CI: 0.82 to 0.93; Subjects with baseline BMI <25 kg/m^2^:; - Breakfast non-consumers: 1.00; - Breakfast consumers: HR 0.78, 95% CI: 0.70 to 0.87; Subjects with baseline BMI ≥25 kg/m^2^:; - Breakfast non-consumers: 1.00; - Breakfast consumers: HR 0.92, 95% CI: 0.85 to 1.00; Summary: An increasing number of EOs in addition to 3 standard meals (breakfast, lunch, and dinner) was associated with a higher risk of 5-kg weight gain.; Consumption of breakfast was found to be associated with a lower risk of weight gain in a cohort of middle-aged and older men. This association was significant in participants who were <25 kg/m^2^ at baseline but not in those ≥25 kg/m^2^. | Model Adjustments:; - Key confounders: age, baseline BMI, smoking status, physical activity; - Other factors to be considered: marital status, work status, weight lifting,; - Other: alcohol intake; TEI adjusted: No; Limitations:; - Race/ethnicity was not accounted for in the analysis; - Selection criteria likely related to FoE and obesity; - FoE data only assessed at baseline with a 10y f/u leading to a concern that changes in exposure status occurred over f/u; - High attrition rate; - Beverages and water were not mentioned; - FoE data collection from 1992 and may not be applicable to current populations and food supply; - Did not adjust for energy intake; Funding sources: NIH
Georgiopoulos, 2017^5^; Prospective Cohort Study, Greece; Analytic N=115; Participant characteristics:; - Age: 47.8y; - Sex: 45% female; - Race/Ethnicity: NR (in Greece); - Habitual eating frequency, median, IQR: 15, 13-18 EF/3 d; 5, 4.3-6 EF/d;; - Smoking: 40%; - Anthropometry: BMI mean 26.2kg/m^2^; waist median 89.5 cm; hip median 102 cm; waist to hip ratio median 0.854; - Total energy intake: ~1823kcal; - Macronutrient content: carbohydrate energy ~39.8%; Lipid energy ~41.3%; protein energy ~38.2;; - Diabetes: 0%; Excluded from study or analysis: history of coronary artery disease, diabetes, liver or endocrine diseases, autoimmune disease, cancer, or active infection; alcohol consumption ≥30g/d; dieting at baseline | Exposure of interest: Frequency of EO: 1-5, ≥6 per day; quartiles of EOs; [underlined: Assessment method and timing]: 3 d dietary records on 2 consecutive weekdays and 1 weekend day at baseline; eating frequency: number of EO/d (mean of 3 d assessments); EO: any EO when food or drink was consumed at least 15 min apart (may include alcohol, soft drinks, kcal-free meals, or coffees and teas eaten in the absence of food.; [underlined: Treatment of non-caloric beverages:] Included as an eating episode; Outcomes and assessment methods:; [underlined: Obesity (at baseline and 5y f/u)]:; BMI: weight and height were measured using a calibrated scale and a wall mounted stadiometer, and BMI was calculated; Waist circumference: measured at the maximal abdominal circumference between the xiphoid process and the iliac crest.; Regional adiposity: Measured by B-mode ultrasonography, and calculated as:; - Subcutaneous fat (Smin): the minimum distance between the skin and linea alba at the level below the xiphoid recess; - Preperitoneal fat (Pmax): the maximum distance between linea alba and the anterior surface of the liver; - Abdominal fat index (AFI): the ratio of Smin to Pmax | [underlined: >6 EOs vs ≤5 EOs (ref):]; - BMI: β=−0.337, p=0.078;; - Waist circumference: β=−0.068, p=0.418;; - Smin: β=0.247, p=0.144;; - Pmax: β=−0.452, p=0.006;; - AFI: β=0.563, p=0.003;; [underlined: Polynomial trend analysis of quartiles of EF:]; - Pmax: quadratic contrast=0.019, p=0.761; - AFI: quadratic contrast=−0.107, p=0.126; [underlined: Quadratic term in regression]:; - Pmax: β =−0.001, p=0.524; - AFI: β =−0.001, p=0.864 | Model Adjustments:; - Key confounders: age, sex, baseline BMI (except in analysis of BMI), smoking; - Other factors to be considered: total energy intake, Hb1Ac; - Other:; TEI adjusted: Yes; Limitations:; - Race/ethnicity (although study took place in Greece) was not accounted for in the analysis; - Selection criteria likely related to FoE and obesity; - FoE data only assessed at baseline with a 5y f/u leading to a concern that changes in exposure status occurred over f/u; - High attrition rate; - Water not mentioned in data collection; Funding sources: NR; Summary: Lower eating frequency, i.e. having ≤5 EOs per day, was significantly associated with decreased preperitoneal fat and an increased abdominal fat index after 5y follow-up.; However, eating frequency was not associated with BMI, waist circumference, or subcutaneous fat.
LaRose, 2019 ^6^; Prospective Cohort Study (using data from a Randomized Controlled Trial, SNAP Trial), United States; Analytic N=599; Participant characteristics:; - Age: 18-35 y; - Sex: 78% female; - Race/Ethnicity: 73% non-Hispanic White; - Habitual eating frequency: 4.7 EOs/d, SD=2.3; breakfast/wk: 5.6, SD=1.8, breakfast daily: 48.4%;; - Smoking: NR; - Anthropometry: NR; - Total energy intake: 1663 kcal, SD=611.13;; - HEI-2010: 67.7, SD=11.0; - Meals away from home/wk: 4.6, SD=3.6;; - Fast food/wk: 1.5, SD=2.3;; - Sugared beverages: ≥1/wk 18.1%; - Diet beverages: ≥1/wk 28.5%; - Alcoholic beverages in past 30 d: 17.5, SD=30.4; binge drinking in past 30 d: 0.9, SD=1.6;; Excluded from study or analysis: <18 or >35 y; BMI <21 or >30 kg/m2; major medical comorbidities; recent weight lost ≥10 lbs; current or planned pregnancy; no internet access; non-English speaking; | Exposure of interest: EOs/d (continuous); [underlined: Assessment method and timing]: Eating pattern questionnaire items assessed eating frequency over the past 30 days (exact question NR); [underlined: Treatment of non-caloric beverages:] NR; Outcomes and assessment methods:; [underlined: Obesity:]; BMI: Weight, height assessed at baseline, 4 mo and 2 y; weight measured after 12 h fast; height measured with wall-mounted stadiometer; BMI calculated | Weight Change from baseline to 4 mo: r=−0.02, p=0.70; Weight Change from baseline to 2 y: r=−0.03, p=0.46; Summary: Eating frequency at baseline was not significantly associated with weight change at 4 mo or 2 y. | Model Adjustments:; - Key confounders: baseline weight; - Other factors to be considered: baseline dietary measure; - Other: trial group assignment.; TEI adjusted: Unsure; model indicates that baseline dietary measure was adjusted for but no other information was provided; Limitations:; - Age, sex, race/ethnicity, smoking were not accounted for in the analysis.; - Selection criteria likely related to FoE and obesity; - Intervention included many health co-interventions that were not accounted for in the FoE analysis; - Exact wording of FoE question was not provided; - FoE data only assessed at baseline with a 2y f/u leading to a concern that changes in exposure status occurred over f/u; Intervention included many health co-interventions that were not accounted for in the FoE analysis; - Unclear whether energy intake was adjusted for; - Unclear if water or beverages were accounted for in FoE assessment; Funding sources: NIH

Table 2 Risk of bias for the randomized controlled trial examining the frequency of eating and growth, size, body composition, and risk of overweight and obesity^iii,iv^

| Randomization | Deviations from intended interventions – effect of assignment | Deviations from intended interventions – per protocol | Missing outcome data | Outcome measurement | Selection of the reported result
Bachman, 2012^1^ | Low | Some Concerns | Low | Low | Low | Low

Table 3 Risk of bias for observational studies examining the frequency of eating and growth, size, body composition, and risk of overweight and obesity^v^

| Confounding | Selection of participants | Classification of exposures | Deviations from intended exposures | Missing data | Outcome measurement | Selection of the reported result
Georgiopoulos, 2017^5^ | Moderate | Serious | Serious | Critical | Low | Moderate | Critical
LaRose, 2019^6^ | Critical | Serious | Critical | Critical | Critical | Low | Critical
Mekary, 2013^3^ | Critical | Serious | Serious | Critical | Moderate | Moderate | Moderate
Ritchie, 2012^2^ | Serious | Moderate | Moderate | Serious | Moderate | Low | Moderate
Van der Heijden, 2007^4^ | Serious | Serious | Serious | Critical | Serious | Serious | Serious

ii Abbreviations: AFI – abdominal fat index; BMI – body mass index; d – days; CI – confidence interval; EO – eating occasion; FFQ – food frequency questionnaire; f/u – follow-up; FoE – frequency of eating; HEI – healthy eating index; HR – hazard ratio; mo – months; N/A – not applicable; NR – not reported; NS – not significant; Pmax – preperitoneal fat; SD – standard deviation; SE – standard error; SES – socioeconomic status; Smin – subcutaneous fat; TEI – total energy intake; wk – weeks; y – years

iii A detailed description of the methodology used for assessing risk of bias is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

iv Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2016 version)” ( Higgins JPT, Sterne JAC, Savović J, Page MJ, Hróbjartsson A, Boutron I, Reeves B, Eldridge S. A revised tool for assessing risk of bias in randomized trials In: Chandler J, McKenzie J, Boutron I, Welch V (editors). Cochrane Methods. Cochrane Database of Systematic Reviews 2016, Issue 10 (Suppl 1). 10.1002/14651858.CD201601. )

v Possible ratings of low, moderate, serious, critical, or no information determined using the “Risk of Bias for Nutrition Observational Studies” tool (RoB-NObs) ( Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC. )