# List of abbreviations

Abbreviation: Full name
BMI: Body mass index
CNPP: Center for Nutrition Policy and Promotion
DPS: Division of Prevention Science
EO: Eating occasion
FNS: Food and Nutrition Service
FoE: Frequency of eating
F/U: Follow-up
HHS: United States Department of Health and Human Services
NESR: Nutrition Evidence Systematic Review
NIH: National Institutes of Health
NR: Not reported
NS: Not significant
ODPHP: Office of Disease Prevention and Health Promotion
ONGA: Office of Nutrition Guidance and Analysis
PCS: Prospective cohort study
SE: Standard error
SES: Socioeconomic status
T2D: Type 2 diabetes
TEI: Total energy intake
USDA: United States Department of Agriculture