# METHODOLOGY

The NESR team used its rigorous, protocol-driven methodology to support the 2020 Dietary Guidelines Advisory Committee in conducting this systematic review.

NESR’s systematic review methodology involves:

- Developing a protocol,
- Searching for and selecting studies,
- Extracting data from and assessing the risk of bias of each included study,
- Synthesizing the evidence,
- Developing conclusion statements,
- Grading the evidence underlying the conclusion statements, and
- Recommending future research.

A detailed description of the methodology used in conducting this systematic review is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews, and can be found in the 2020 Dietary Guidelines Advisory Committee Report, Part C: Methodology.^v^ This systematic review was peer reviewed by Federal scientists, and information about the peer review process can also be found in the Committee’s Report, Part C. Methodology. Additional information about this systematic review, including a description of and rationale for any modifications made to the protocol can be found in the 2020 Dietary Guidelines Advisory Committee Report, Chapter 13. Frequency of Eating.

Below are details of the final protocol for the systematic review described herein, including the:

- Analytic framework
- Literature search and screening plan
- Literature search and screening results

## ANALYTIC FRAMEWORK

The analytic framework (Figure 1) illustrates the overall scope of the systematic review, including the population, the interventions and/or exposures, comparators, and outcomes of interest. It also includes definitions of key terms and identifies key confounders considered in the systematic review. The inclusion and exclusion criteria that follow provide additional information about how parts of the analytic framework were defined and operationalized for the review.

Figure 1 Analytic framework

An analytic framework visually represents the overall scope of the systematic review question, and depicts the contributing elements that were examined and evaluated, including the target population, exposure, comparison, outcomes, and key confounders. This is the analytic framework for the systematic review question on the relationship between the frequency of eating and risk of type 2 diabetes. For this systematic review, the target population considered was children through older adults who were healthy and/or at risk of chronic disease. The interventions or exposures considered were frequency of eating, or the number of daily eating occasions. The intermediate outcomes considered were glucose, insulin, hemoglobin A1C, prediabetes. The endpoint outcome considered was type 2 diabetes. The key confounders were sex, age, race/ethnicity, habitual eating frequency, physical activity, smoking, anthropometry. The other factors to be considered were socioeconomic status, cultural practices, total energy intake, diet energy density, energy state of the diet (restriction/surplus), energy balance (total energy intake/total energy expenditure), chrononutrition factors (time of day, (consistency of) habitual eating frequency, and duration between ingestive events and/or ingestive periods), portion size, macronutrient content, location of eating occasion, specialized diet including all-liquids diet, eating environment (who you eat with, work/school/exercise schedule), holiday eating (seasonal), sleep schedule (shift work), secondary eating, dentition, hydration status, pregnancy status, pubertal status, menopausal status, family history of type 2 diabetes, medication and substance use, and biochemical changes.

## LITERATURE SEARCH AND SCREENING PLAN

### Inclusion and exclusion criteria

This table provides the inclusion and exclusion criteria for the systematic review. The inclusion and exclusion criteria are the set of characteristics used to determine which articles identified in the literature search were included in or excluded from the systematic review.

Table 3 Inclusion and exclusion criteria

Category | Inclusion Criteria | Exclusion Criteria
Study design | - Randomized controlled trials; - Non-randomized controlled trials, including quasi-experimental and controlled before and after studies; - Prospective cohort studies; - Retrospective cohort studies; - Nested case-control studies | - Uncontrolled trials; - Case-control studies; - Cross-sectional studies; - Uncontrolled before-and-after studies; - Narrative reviews; - Systematic reviews; - Meta-analyses
Intervention/exposure | Frequency of eating:; - Number of daily eating occasions | - Studies that only examine frequency of intake of a single food, beverage or category of foods or beverages (i.e. frequency of milk consumption, frequency of seafood consumption); - Studies that do not have eating occasions across the day
Comparator | - Different number of daily eating occasions | - N/A
Outcomes | Intermediate Outcomes:; - Glucose; - Insulin; - Hemoglobin A1C; - Prediabetes; Endpoint Outcomes:; - Type 2 diabetes | - Type 1 diabetes
Date of publication | - January 2000 – September 2019 | - Articles published prior to or after January 2000 – September 2019
Publication status | - Articles published in peer-reviewed journals | - Articles that have not been peer-reviewed and are not published in peer-reviewed journals (e.g. unpublished data, manuscripts, reports, abstracts, pre-prints, and conference proceedings)
Language of publication | - Articles published in English | - Articles published in languages other than English
Country^vi^ | - Studies conducted in countries ranked as high or very high human development | - Studies conducted in countries ranked as medium or lower human development
Study participants | - Human participants; - Males; - Females; - Females during pregnancy and the post-partum period | - Non-human participants (i.e., animals or in-vitro models)
Age of study participants | - Age at intervention or exposure:; ○ Children and adolescents (2-18 years); ○ Adults (19-64 years); ○ Older adults (ages 65 and older); - Age at outcome:; ○ Children and adolescents (2-18 years); ○ Adults (19-64 years); - Older adults (ages 65 and older) | - Age at intervention or exposure:; ○ Infants and toddlers (0-24 months old); - Age at outcome:; - Infants and toddlers (0-24 months old)
Health status of study participants | - Studies that enroll participants who are healthy and/or at risk for chronic disease, including those with obesity; - Studies that enroll some participants diagnosed with a disease; - Studies that enroll some participants diagnosed with type 2 diabetes. | - Studies that exclusively enroll participants diagnosed with a disease, or hospitalized with an illness or injury (For this criterion, studies that exclusively enroll participants with obesity will not be excluded); - Studies that exclusively enroll participants with type 2 diabetes (i.e., studies that aim to treat participants who have already been diagnosed with type 2 diabetes); - Studies that exclusively enroll subjects post bariatric surgery
Eating frequency data collection for intervention studies | - Data collection for eating frequency that occurs on at least 2 occasions, including baseline and during or after the intervention.; ○ Each occasion encompasses a minimum of 3, 24-hour periods or a questionnaire that covers at least 3 days addressing eating frequency.; ▪ (e.g., 3, 24-h dietary recalls reporting ingestive events); ▪ (e.g., 1 eating frequency questionnaire documenting eating frequency for the past month) | - Data collection for eating frequency that occurs on fewer than 2 occasions, and encompasses fewer than 3, 24-hour periods
Eating frequency data collection for observational studies | - Data collection for eating frequency that encompasses a minimum of 3, 24-hour periods; ○ (e.g., 3, 24-h dietary recalls reporting each ingestive event); ○ (e.g., 1 eating frequency questionnaire documenting eating frequency for the past month) | - Data collection for eating frequency that encompasses fewer than 3, 24-hour periods
Size of study groups for intervention studies | - 15 or greater participants for studies using within-subject analyses, or; - 30 or greater participants for studies using between-subject analysis, or; - A power calculation included | - Fewer than 15 participants for studies using within-subject analyses, or; - Fewer than 30 participants for studies using between-subject analysis, or; - No power calculation reported

### Electronic databases and search terms

#### PubMed

- Provider: U.S. National Library of Medicine
- Date(s) searched: September 17 2019
- Date range searched: January 1, 2000-September 17 2019
- Search Terms:
  - #1 - “frequency of eating” OR eating frequenc* OR “frequent eating” OR feeding frequenc* OR “Meals”[Mesh] OR meal frequenc* OR “meal timing” OR “meal time” OR mealtim* OR daily meal* OR dinnertim* OR dinner pattern* OR “night eating” OR evening meal* OR eating occasion* OR irregular eat* OR snack frequenc* OR snacking frequenc* OR snacking pattern* OR snacking behavior* OR “Fasting”[Mesh] OR “intermittent fasting” OR fasting diet* OR “alternate-day fasting” OR “meal skipping” OR “breakfast skipping” OR skipping breakfast* OR “Feeding Behavior”[Mesh:noexp] OR feeding behavior*[tiab] OR eating episode* OR eating pattern* OR eating habit* OR eating tim* OR “eating alone” OR time restricted feeding* OR feeding pattern* OR meal profile* OR meal pattern* OR meal environment* OR chrononutrition OR intermittent energy restriction* OR intermittent diet*
  - #2 - "Cardiovascular Diseases”[Mesh:noexp] OR cardiovascular disease*[tiab] OR coronary artery disease[tiab] OR heart disease*[tiab] OR “Heart Failure”[Mesh] OR heart failure[tiab] OR “Myocardial Infarction”[Mesh] OR myocardial infarction*[tiab] OR “Myocardial Ischemia”[Mesh] OR Myocardial Ischemia*[tiab] OR “Stroke”[Mesh] OR stroke[tiab] OR angina[tiab] OR heart attack[tiab] OR “Venous Thrombosis”[Mesh] OR venous thrombosis[tiab] OR hypertension[tiab] OR high blood pressure[tiab] OR “Lipids/blood”[Mesh] OR “Cholesterol, HDL”[Mesh] OR HDL cholesterol[tiab] OR “Cholesterol, LDL”[Mesh] OR LDL cholesterol[tiab] OR total cholesterol[tiab] OR “Triglycerides”[Mesh] OR triglycerides[tiab]
  - #3 - “Diabetes Mellitus, Type 2”[Mesh] OR Type 2 diabetes[tiab] OR T2D[tiab] OR adult onset diabetes[tiab] OR “Prediabetic State”[Mesh] OR prediabet*[tiab] OR pre diabet* OR “Insulin Resistance”[Mesh] OR insulin resistance[tiab] OR “Glucose Intolerance”[Mesh] OR glucose intolerance[tiab] OR glucose tolerance[tiab] OR “Glycated Hemoglobin A”[Mesh] OR hemoglobin A1c[ti] OR “Hyperglycemia”[Mesh] OR “Hypoglycemia”[Mesh] OR ((impaired fasting[tiab] OR “Diabetes Mellitus”[Mesh:noexp]) AND (glucose[tiab] OR glycemi*[tiab] OR high blood sugar[tiab] OR low blood sugar[tiab]
  - #4 - “Body Weights and Measures”[Mesh] OR “Body Weight”[Mesh] OR body weight[tiab] OR “Overnutrition”[Mesh:NoExp] OR overnutrition[tiab] OR body weight[tiab] OR weight status[tiab] OR obesity[tiab] OR obese[tiab] OR overweight[tiab] OR body mass index[tiab] OR BMI[tiab] OR underweight[tiab] OR wasting[tiab] OR healthy weight[tiab] OR “Body Composition”[Mesh] OR body composition[tiab] OR body fat[tiab] OR fat mass[tiab] OR fat free mass[tiab] OR “Adipose Tissue”[Mesh] OR “Adiposity”[Mesh] OR adipos*[tiab] OR anthropometry[tiab] OR anthropometric*[tiab] OR body height[tiab] OR stunting[tiab] OR stunted[tiab] OR “Growth Charts”[Mesh] OR growth chart*[tiab] OR waist circumference[tiab] OR head circumference[tiab] OR arm circumference[tiab] OR thigh circumference[tiab] OR neck circumference[tiab] OR “Gestational Weight Gain”[Mesh] OR “Weight Gain”[Mesh:NoExp] OR weight gain[tiab] OR “Body Size”[Mesh] OR “body size”[tiab] OR weight change[tiab] OR weight changes[tiab] OR “Weight Loss”[Mesh] OR weight loss*[tiab] OR weight reduc*[tiab] OR “Weight Reduction Programs”[Mesh] OR “Body-Weight Trajectory”[Mesh] OR weight maint* OR “Diet, Reducing”[Mesh] OR diet reduc*[tiab] OR weight cycling[tiab] OR weight decreas*[tiab] OR weight watch*[tiab] OR weight control*[tiab] OR weight retention[tiab] OR (weight[tiab] AND (reduction OR reduced OR reducing OR loss OR losses OR maintenanc* OR maintain*[tiab] OR decreas*[tiab] OR watch OR control*[tiab] OR change*[tiab] OR gain[tiab]))
  - #5 - (#2 OR #3 OR #4)
  - #6 - (#1 AND #5)
  - #7 - (#1 AND #5) NOT (“Animals”[Mesh] NOT (“Animals”[Mesh] AND “Humans”[Mesh])) NOT (editorial[ptyp] OR comment[ptyp] OR news[ptyp] OR letter[ptyp] OR review[ptyp] OR systematic review[ptyp] OR systematic review[ti] OR meta-analysis[ptyp] OR meta-analysis[ti] OR meta-analyses[ti] OR retracted publication[ptyp] OR retraction of publication[ptyp] OR retraction of publication[tiab] OR retraction notice[ti]) Filters: Publication date from 2000/01/01 to 2019/09/17; English

#### Cochrane Central Register of Controlled Trials (CENTRAL)

- Provider: John Wiley & Sons
- Date(s) searched: September 17, 2019
- Date range searched: January 1, 2000-September 17, 2019
- Search Terms:
  - #1 - [mh Meals] OR [mh Fasting] OR [mh ^”Feeding Behavior”]
  - #2 - “ frequency of eating” OR “eating frequenc*” OR “frequent eating” OR “feeding frequenc*” OR “meal frequenc*” OR “meal timing” OR “meal time” OR mealtim* OR “daily meal*” OR dinnertim* OR “dinner pattern*” OR “night eating” OR “evening meal*” OR “eating occasion*” OR “irregular eat*” OR “snack frequenc*” OR “snacking frequenc*” OR “snacking pattern*” OR “snacking behavior*” OR “intermittent fasting” OR “fasting diet*” OR “alternate-day fasting” OR “meal skipping” OR “breakfast skipping” OR “skipping breakfast*” OR “feeding behavior*” OR “eating episode*” OR “eating pattern*” OR “eating habit*” OR “eating tim*” OR “eating alone” OR “time restricted feeding*” OR “feeding pattern*” OR “meal profile*” OR “meal pattern*” OR “meal environment*” OR chrono-nutrition OR “intermittent energy restriction*” OR “intermittent diet*”
  - #3 - #1 OR #2
  - #4 - [mh ^”Cardiovascular Diseases”] OR [mh “Heart Failure”] OR [mh “Myocardial Infarction”] OR [mh “Myocardial Ischemia”] OR [mh Stroke] OR [mh “Venous Thrombosis”] OR [mh Lipids/BL] OR [mh “Cholesterol, HDL”] OR [mh “Cholesterol, LDL”] OR [mh Triglycerides]
  - #5 - (“cardiovascular disease*” OR “coronary artery disease” OR “heart disease” OR “heart failure” OR “myocardial infarction*” OR “myocardial ischemia*” OR stroke OR angina OR “heart attack” OR “venous thrombosis” OR “hypertension” OR “high blood pressure” OR “HDL cholesterol” OR “LDL cholesterol” OR “total cholesterol” OR triglycerides):ti,ab,kw
  - #6 - #4 OR #5
  - #7 - [mh “Diabetes Mellitus, Type 2”] OR [mh “Prediabetic State”] OR [mh “Insulin Resistance”] OR [mh “Glucose Intolerance”] OR [mh “Glycated Hemoglobin A”] OR [mh Hyperglycemia] OR [mh Hypoglycemia]
  - #8 - (“Type 2 diabetes” OR T2D OR “adult onset diabetes” OR prediabet* OR pre diabet* OR “insulin resistance” OR “glucose intolerance” OR “glucose tolerance” OR “hemoglobin A1c”):ti,ab,kw
  - #9 - ((“impaired fasting” OR [mh ^”Diabetes Mellitus”]) AND (glucose OR glycemi* OR “high blood sugar” OR “low blood sugar”))
  - #10 - #7 OR #8 OR #9
  - #11 - [mh “Body Weights and Measures”] OR [mh “Body Weight”] OR [mh ^Overnutrition] OR [mh “Body Composition”] OR [mh “Adipose Tissue”] OR [mh Adiposity] OR [mh “Growth Charts”] OR [mh “Gestational Weight Gain”] OR [mh ^”Weight Gain”] OR [mh “Body Size”] OR [mh “Weight Loss”] OR [mh “Weight Reduction Programs”] OR [mh “Body-Weight Trajectory”] OR [mh “Diet, Reducing”]
  - #12 - “body weight” OR overnutrition OR “body weight” OR “weight status” OR obesity OR obese OR overweight OR “body mass index” OR BMI OR underweight OR wasting OR “healthy weight” OR “body composition” OR “body fat” OR “fat mass” OR “fat free mass” OR adipos* OR anthropometry OR anthropometric* OR “body height” OR stunting OR stunted OR “growth chart*” OR “waist circumference” OR “head circumference” OR “arm circumference” OR “thigh circumference” OR “neck circumference” OR “weight gain” OR “body size” OR “weight change” OR “weight changes” OR “weight loss*” OR “weight reduc*” OR “weight maint*” OR “diet reduc*” OR “weight cycling” OR “weight decreas*” OR “weight watch*” OR “weight control*” OR “weight retention”
  - #13 - ((weight NEAR/4 (reduction OR reduced OR reducing OR loss OR losses OR maintenanc* OR maintain* OR decreas* OR watch OR control* OR change* OR gain))):ti,ab,kw
  - #14 - #11 OR #12 OR #13
  - #15 - #6 OR #10 OR #14
  - #16 - #3 AND #15” with Publication Year from 2000 to 2019, in Trials (Word variations have been searched)

#### Embase

- Provider: Elsevier
- Date(s) searched: September 17, 2019
- Date range searched: January 1, 2000-September 17, 2019
- Search Terms:
  - #1 - ‘meal’/exp OR ‘fasting’/exp OR ‘feeding behavior’/de
  - #2 - ‘frequency of eating’:ab,ti OR ‘eating frequenc*’:ab,ti OR ‘frequent eating’:ab,ti OR ‘feeding frequenc*’:ab,ti OR ‘meal frequenc*’:ab,ti OR ‘meal timing’:ab,ti OR ‘meal time’:ab,ti OR mealtim*:ab,ti OR ‘daily meal*’:ab,ti OR dinnertim*:ab,ti OR ‘dinner pattern*’:ab,ti OR ‘night eating’:ab,ti OR ‘evening meal*’:ab,ti OR ‘eating occasion*’:ab,ti OR ‘irregular eat*’:ab,ti OR ‘snack frequenc*’:ab,ti OR ‘snacking frequenc*’:ab,ti OR ‘snacking pattern*’:ab,ti OR ‘snacking behavior*’:ab,ti OR ‘intermittent fasting’:ab,ti OR ‘fasting diet*’:ab,ti OR ‘alternate-day fasting’:ab,ti OR ‘meal skipping’:ab,ti OR ‘breakfast skipping’:ab,ti OR ‘skipping breakfast*’:ab,ti OR ‘feeding behavior*’:ab,ti OR ‘eating episode*’:ab,ti OR ‘eating pattern*’:ab,ti OR ‘eating habit*’:ab,ti OR ‘eating tim*’:ab,ti OR ‘eating alone’:ab,ti OR ‘time restricted feeding*’:ab,ti OR ‘feeding pattern*’:ab,ti OR ‘meal profile*’:ab,ti OR ‘meal pattern*’:ab,ti OR ‘meal environment*’:ab,ti OR ‘chrono nutrition’:ab,ti OR ‘intermittent energy restriction*’:ab,ti OR ‘intermittent diet*’:ab,ti
  - #3 - #1 OR #2
  - #4 - ‘cardiovascular disease’/de OR ‘heart failure’/exp OR ‘heart infarction’/exp OR ‘heart muscle ischemia’/exp OR ‘cerebrovascular accident’/exp OR ‘vein thrombosis’/exp OR ‘high density lipoprotein cholesterol’/de OR ‘low density lipoprotein cholesterol’/de OR ‘triacylglycerol’/exp
  - #5 - ‘cardiovascular disease*’:ab,ti OR ‘coronary artery disease’:ab,ti OR ‘heart disease’:ab,ti OR ‘heart failure’:ab,ti OR ‘myocardial infarction*’:ab,ti OR ‘myocardial ischemia*’:ab,ti OR stroke:ab,ti OR angina:ab,ti OR ‘heart attack’:ab,ti OR ‘venous thrombosis’:ab,ti OR ‘hypertension’:ab,ti OR ‘high blood pressure’:ab,ti OR ‘hdl cholesterol’:ab,ti OR ‘ldl cholesterol’:ab,ti OR ‘total cholesterol’:ab,ti OR triglycerides:ab,ti
  - #6 - #4 OR #5
  - #7 - ‘non insulin dependent diabetes mellitus’/exp OR ‘impaired glucose tolerance’/exp OR ‘insulin resistance’/de OR ‘glucose intolerance’/de OR ‘glycosylated hemoglobin’/exp OR ‘hyperglycemia’/de OR ‘hypoglycemia’/exp
  - #8 - ‘type 2 diabetes’:ab,ti OR t2d:ab,ti OR ‘adult onset diabetes’:ab,ti OR prediabet*:ab,ti OR ‘pre diabet*’:ab,ti OR ‘insulin resistance’:ab,ti OR ‘glucose intolerance’:ab,ti OR ‘glucose tolerance’:ab,ti OR ‘hemoglobin a1c’:ab,ti
  - #9 - ((‘impaired fasting’ OR ‘diabetes mellitus]’) NEAR/4 (glucose OR glycemi* OR ‘high blood sugar’ OR ‘low blood sugar’)):ab,ti
  - #10 - #7 OR #8 OR #9
  - #11 - ‘weight, mass and size’/exp OR ‘body weight’/exp OR ‘overnutrition’/de OR ‘body composition’/exp OR ‘adipose tissue’/exp OR ‘growth chart’/de OR ‘gestational weight gain’/de OR ‘body weight gain’/de OR ‘body size’/de OR ‘body weight loss’/exp OR ‘weight loss program’/de OR ‘weight trajectory (body weight)’/de OR ‘low calorie diet’/exp
  - #12 - overnutrition:ab,ti OR ‘body weight’:ab,ti OR ‘weight status’:ab,ti OR obesity:ab,ti OR obese:ab,ti OR overweight:ab,ti OR ‘body mass index’:ab,ti OR bmi:ab,ti OR underweight:ab,ti OR wasting:ab,ti OR ‘healthy weight’:ab,ti OR ‘body composition’:ab,ti OR ‘body fat’:ab,ti OR ‘fat mass’:ab,ti OR ‘fat free mass’:ab,ti OR adipos*:ab,ti OR anthropometry:ab,ti OR anthropometric*:ab,ti OR ‘body height’:ab,ti OR stunting:ab,ti OR stunted:ab,ti OR ‘growth chart*’:ab,ti OR ‘waist circumference’:ab,ti OR ‘head circumference’:ab,ti OR ‘arm circumference’:ab,ti OR ‘thigh circumference’:ab,ti OR ‘neck circumference’:ab,ti OR ‘weight gain’:ab,ti OR ‘body size’:ab,ti OR ‘weight change’:ab,ti OR ‘weight changes’:ab,ti OR ‘weight loss*’:ab,ti OR ‘weight reduc*’:ab,ti OR ‘weight maint*’:ab,ti OR ‘diet reduc*’:ab,ti OR ‘weight cycling’:ab,ti OR ‘weight decreas*’:ab,ti OR ‘weight watch*’:ab,ti OR ‘weight control*’:ab,ti OR ‘weight retention’:ab,ti
  - #13 - (weight NEAR/4 (reduction OR reduced OR reducing OR loss OR losses OR maintenanc* OR maintain* OR decreas* OR watch OR control* OR change* OR gain)):ab,ti
  - #14 - #11 OR #12 OR #13
  - #15 - #6 OR #10 OR #14
  - #16 - #3 AND #15
  - #17 - #3 AND #15 AND ([article]/lim OR [article in press]/lim) AND [humans]/lim AND [english]/lim AND [2000-2019]/py NOT ([conference abstract]/lim OR [conference review]/lim OR [conference paper]/lim OR [editorial]/lim OR [erratum]/lim OR [letter]/lim OR [note]/lim OR [review]/lim OR [systematic review]/lim OR [meta analysis]/lim)

#### CINAHL Plus (Cumulative Index to Nursing and Allied Health Literature)

- Provider: EBSCOhost
- Date(s) searched: September 24, 2019
- Date range searched: January 1, 2000-September 24, 2019
- Search Terms:
  - #S1 - (MH “Meals+”) OR (MH “Fasting”) OR (MH “Eating Behavior”)
  - #S2 - “frequency of eating” OR “eating frequenc*” OR “frequent eating” OR “feeding frequenc*” OR “meal frequenc*” OR “meal timing” OR “meal time” OR mealtim* OR “daily meal*” OR dinnertim* OR “dinner pattern*” OR “night eating” OR “evening meal*” OR “eating occasion*” OR “irregular eat*” OR “snack frequenc*” OR “snacking frequenc*” OR “snacking pattern*” OR “snacking behavior*” OR “intermittent fasting” OR “fasting diet*” OR “alternate-day fasting” OR “meal skipping” OR “breakfast skipping” OR “skipping breakfast*” OR “feeding behavior*” OR “eating episode*” OR “eating pattern*” OR “eating habit*” OR “eating tim*” OR “eating alone” OR “time restricted feeding*” OR “feeding pattern*” OR “meal profile*” OR “meal pattern*” OR “meal environment*” OR chrono-nutrition OR “intermittent energy restriction*” OR “intermittent diet*”
  - #S3 - S1 OR S2
  - #S4 - (MH “Cardiovascular Diseases”) OR (MH “Heart Failure+”) OR (MH “Myocardial Infarction+”) OR (MH “Myocardial Ischemia+”) OR (MH “Stroke+”) OR (MH “Venous Thrombosis+”) OR (MH “Lipids/BL”) OR (MH “Lipoproteins, HDL Cholesterol”) OR (MH “Lipoproteins, LDL Cholesterol”) OR (MH “Triglycerides”)
  - #S5 - “cardiovascular disease*” OR “coronary artery disease” OR “heart disease*”OR “heart failure” OR “myocardial infarction*” OR “myocardial Ischemia*” OR stroke OR angina OR “heart attack” OR “venous thrombosis” OR hypertension OR “high blood pressure” OR “HDL cholesterol” OR “LDL cholesterol” OR “total cholesterol” OR triglycerides
  - #S6 - S4 OR S5
  - #S7 - (MH “Diabetes Mellitus, Type 2”) OR (MH “Prediabetic State”) OR (MH “Insulin Resistance+”) OR (MH “Glucose Intolerance”) OR (MH “Hemoglobin A, Glycosylated”) OR (MH “Hyperglycemia+”) OR (MH “Hypoglycemia+”)
  - #S8 - (“Type 2 diabetes” OR T2D OR “adult onset diabetes” OR prediabet* OR pre diabet* OR “insulin resistance” OR “glucose intolerance” OR “glucose tolerance” OR “hemoglobin A1c”)
  - #S9 - ((MH “Diabetes Mellitus” OR “impaired fasting”) N4 (glucose OR glycemi* OR “high blood sugar” OR “low blood sugar”))
  - #S10 - S7 OR S8 OR S9
  - #S11 - (MH “Body Weights and Measures+”) OR (MH “Body Weight+”) OR (MH “Body Composition+”) OR (MH “Adipose Tissue”) OR (MH “Gestational Weight Gain”) OR (MH “Weight Gain+”) OR (MH “Body Size”) OR (MH “Weight Loss+”) OR (MH “Weight Reduction Programs”) OR (MH “Body Weight Changes”) OR (MH “Diet, Reducing”)
  - #S12 - “body weight” OR overnutrition OR “body weight” OR “weight status” OR obesity OR obese OR overweight OR “body mass index” OR BMI OR underweight OR wasting OR “healthy weight” OR “body composition” OR “body fat” OR “fat mass” OR “fat free mass” OR adipos* OR anthropometry OR anthropometric* OR “body height” OR stunting OR stunted OR “growth chart*” OR “waist circumference” OR “head circumference” OR “arm circumference” OR “thigh circumference” OR “neck circumference” OR “weight gain” OR “body size” OR “weight change” OR “weight changes” OR “weight loss*” OR “weight reduc*” OR “weight maint*” OR “diet reduc*” OR “weight cycling” OR “weight decreas*” OR “weight watch*” OR “weight control*” OR “weight retention”
  - #S13 - ((weight N4 (reduction OR reduced OR reducing OR loss OR losses OR maintenanc* OR maintain* OR decreas* OR watch OR control* OR change* OR gain))
  - #S14 - S11 OR S12 OR S13
  - #S15 - S6 OR S10 OR S14
  - #S16 - (S3 AND S15) NOT (MH “Literature Review” OR MH “Meta Analysis” OR MH “Systematic Review” OR MH “News” OR MH “Retracted Publication” OR MH “Retraction of Publication) Publication Year: 2000-2019; Peer Reviewed; English Language; Human

## LITERATURE SEARCH AND SCREENING RESULTS

The flow chart (Figure 2) below illustrates the literature search and screening results for articles examining the systematic review question. The literature search was conducted to identify articles for 5 different, but related systematic reviews on frequency of eating and growth, size, and body composition, cardiovascular disease, type 2 diabetes, post-partum weight loss, and gestational weight gain. The results of the electronic database searches, after removal of duplicates, were screened independently by two NESR analysts using a stepwise process by reviewing titles, abstracts, and full-texts to determine which articles met the inclusion criteria. Refer to Table 4 for the rationale for exclusion for each excluded full-text article. A manual search was done to find articles that were not identified when searching the electronic databases; all manually identified articles were also screened to determine whether they meet criteria for inclusion.

The literature search and screening results from multiple questions on frequency of eating were combined for efficiency because of topical overlap. The searches were designed to comprehensively identify relevant literature in all examined systematic reviews questions to avoid screening the same results multiple times.

Figure 2 Flow chart of literature search and screening results

This flow chart illustrates the literature search and screening results for articles examining the relationship between the frequency of eating and growth, size, and body composition, and overweight and obesity, cardiovascular disease, type 2 diabetes, postpartum weight loss, and gestational weight gain. A total of 6 articles were included in the systematic review on growth, size, and body composition at the end of the search and screening process. A total of 2 articles were included in the systematic review on cardiovascular disease at the end of the search and screening process. A total of 2 articles were included in the systematic review on type 2 diabetes at the end of the search and screening process. A total of 1 article was included in the systematic review on postpartum weight loss at the end of the search and screening process. A total of 0 articles were included in the systematic review on gestational weight gain at the end of the search and screening process.

### Excluded articles

The table below lists the articles excluded after full-text screening, and includes a column for the rationale for study exclusion based on the criteria in Table 3. At least one reason for exclusion is provided for each article, though this may not reflect all possible reasons for exclusion. Information about articles excluded after title and abstract screening is available upon request.

Table 4 Articles excluded after full text screening with rationale for exclusion

| Citation | Rationale
1 | A little at a time: eating and exercising in bits and pieces. Harv Mens Health Watch. 2006. 11:6–7 https://www.ncbi.nlm.nih.gov/pubmed/17153760 | Publication Status
2 | Abdullah NF, Teo PS, Foo LH. Ethnic Differences in the Food Intake Patterns and Its Associated Factors of Adolescents in Kelantan, Malaysia. Nutrients. 2016;8(9). https://www.ncbi.nlm.nih.gov/pubmed/27626444. | Study Design
3 | Abendroth A, Michalsen A, Ludtke R, Ruffer A, Musial F, Dobos GJ, Langhorst J. Changes of Intestinal Microflora in Patients with Rheumatoid Arthritis during Fasting or a Mediterranean Diet. Forsch Komplementmed. 2010. 17:307–13 https://www.ncbi.nlm.nih.gov/pubmed/21196744 | Publication Status
4 | Adachi Y, Sato C, Yamatsu K, Ito S, Adachi K, Yamagami T. A randomized controlled trial on the long-term effects of a 1-month behavioral weight control program assisted by computer tailored advice. Behav Res Ther. 2007. 45:459–70 https://www.ncbi.nlm.nih.gov/pubmed/16713991 | Intervention/Exposure, Daily Eating Occasions Not Reported
5 | Adawi M, Damiani G, Bragazzi NL, Bridgewood C, Pacifico A, Conic RRZ, et al. The Impact of Intermittent Fasting (Ramadan Fasting) on Psoriatic Arthritis Disease Activity, Enthesitis, and Dactylitis: A Multicentre Study. Nutrients. 2019;11(3). https://www.ncbi.nlm.nih.gov/pubmed/30871045. | Daily Eating Occasions Not Reported, Eating Frequency Data Collection
6 | Adegboye AR, Rossner S, Neovius M, Lourenco PM, Linne Y. Relationships between prenatal smoking cessation, gestational weight gain and maternal lifestyle characteristics. Women Birth. 2010. 23:29–35 https://www.ncbi.nlm.nih.gov/pubmed/19586807 | Intervention/Exposure
7 | Affenito SG, Thompson D, Dorazio A, Albertson AM, Loew A, Holschuh NM. Ready-to-eat cereal consumption and Study Design the School Breakfast Program: relationship to nutrient intake and weight. J Sch Health. 2013. 83:28–35 https://www.ncbi.nlm.nih.gov/pubmed/23253288 | Study Design
8 | Affenito SG, Thompson DR, Barton BA, Franko DL, Daniels SR, Obarzanek E, Schreiber GB, Striegel-Moore RH. Breakfast consumption by African-American and white adolescent girls correlates positively with calcium and fiber intake and negatively with body mass index. J Am Diet Assoc. 2005. 105:938–45 https://www.ncbi.nlm.nih.gov/pubmed/15942545 | Daily Eating Occasions Not Reported
9 | Affenito SG. Breakfast: A Missed Opportunity. Journal of the American Dietetic Association. 2007;107(4):565–9. https://www.ncbi.nlm.nih.gov/pubmed/17383260. | Study Design
10 | Afrasiabi A, Hassanzadeh S, Sattarivand R, Mahboob S. Effects of Ramadan fasting on serum lipid profiles on 2 hyperlipidemic groups with or without diet pattern. Saudi Med J. 2003. 24:23–6 https://www.ncbi.nlm.nih.gov/pubmed/12590268 | Daily Eating Occasions Not Reported, Country
11 | Afrasiabi A, Hassanzadeh S, Sattarivand R, Nouri M, Mahbood S. Effects of low fat and low calorie diet on plasma lipid levels in the fasting month of Ramadan. Saudi Med J. 2003. 24:184–8 https://www.ncbi.nlm.nih.gov/pubmed/12682685 | Intervention/Exposure, Daily Eating Occasions Not Reported
12 | Agras WS, Hammer LD, McNicholas F, Kraemer HC. Risk factors for childhood overweight: a prospective study from birth to 9.5 years. J Pediatr. 2004. 145:20–5 https://www.ncbi.nlm.nih.gov/pubmed/15238901 | Intervention/Exposure, Daily Eating Occasions Not Reported
13 | Aila Gustafsson S, Edlund B, Kjellin L, Norring C. Risk and protective factors for disturbed eating in adolescent girls - aspects of perfectionism and attitudes to eating and weight. Eur Eat Disord Rev. 2009. 17:380–9 https://www.ncbi.nlm.nih.gov/pubmed/19378349 | Intervention/Exposure, Daily Eating Occasions Not Reported
14 | Ajabnoor GM, Bahijri S, Borai A, Abdulkhaliq AA, Al-Aama JY, Chrousos GP. Health impact of fasting in Saudi Arabia during Ramadan: association with disturbed circadian rhythm and metabolic and sleeping patterns. PLoS One. 2014. 9:e96500 https://www.ncbi.nlm.nih.gov/pubmed/24810091 | Daily Eating Occasions Not Reported
15 | Ajabnoor GM, Bahijri S, Shaik NA, Borai A, Alamoudi AA, Al-Aama JY, Chrousos GP. Ramadan fasting in Saudi Arabia is associated with altered expression of CLOCK, DUSP and IL-1alpha genes, as well as changes in cardiometabolic risk factors. PLoS One. 2017. 12:e0174342 https://www.ncbi.nlm.nih.gov/pubmed/28384165 | Daily Eating Occasions Not Reported
16 | Akanji AO, Mojiminiyi OA, Abdella N. Beneficial changes in serum apo A-1 and its ratio to apo B and HDL in stable hyperlipidaemic subjects after Ramadan fasting in Kuwait. Eur J Clin Nutr. 2000. 54:508–13 https://www.ncbi.nlm.nih.gov/pubmed/10878654 | Intervention/Exposure, Daily Eating Occasions Not Reported
17 | Akhan G, Kutluhan S, Koyuncuoglu HR. Is there any change of stroke incidence during Ramadan?. Acta Neurol Scand. 2000. 101:259–61 https://www.ncbi.nlm.nih.gov/pubmed/10770523 | Intervention/Exposure, Daily Eating Occasions Not Reported
18 | Akimoto-Gunther L, Hubler M, Santos M, Carolino I, Sonoo N, Botti B, Mota D, Takahachi G. Effects of re-education in eating habits and physical activity on the lipid profile of obese teenagers. Clin Chem Lab Med. 2002. 40:460–2 https://www.ncbi.nlm.nih.gov/pubmed/12113288 | Study Design, Intervention/Exposure, Daily Eating Occasions Not Reported
19 | Aksungar FB, Eren A, Ure S, Teskin O, Ates G. Effects of intermittent fasting on serum lipid levels, coagulation status and plasma homocysteine levels. Ann Nutr Metab. 2005. 49:77–82 https://www.ncbi.nlm.nih.gov/pubmed/15802901 | Intervention/Exposure, Daily Eating Occasions Not Reported
20 | Aksungar FB, Sarikaya M, Coskun A, Serteser M, Unsal I. Comparison of Intermittent Fasting Versus Caloric Restriction in Obese Subjects: A Two Year Follow-Up. J Nutr Health Aging. 2017. 21:681–685 https://www.ncbi.nlm.nih.gov/pubmed/28537332 | Study Design, Size of Study Groups
21 | Aksungar FB, Topkaya AE, Akyildiz M. Interleukin-6, C-reactive protein and biochemical parameters during prolonged intermittent fasting. Ann Nutr Metab. 2007. 51:88–95 https://www.ncbi.nlm.nih.gov/pubmed/17374948 | Daily Eating Occasions Not Reported
22 | Aktas MF, Mahler A, Hamm M, Perger G, Simon F, Westenhofer J, Luft FC, Boschmann M. Lifestyle interventions in Muslim patients with metabolic syndrome-a feasibility study. Eur J Clin Nutr. 2019. 73:805–808 https://www.ncbi.nlm.nih.gov/pubmed/30538299 | Intervention/Exposure
23 | Al Assaad RG, Bachir R, El Sayed MJ. Impact of Ramadan on emergency department visits and on medical emergencies. Eur J Emerg Med. 2018. 25:440–444 https://www.ncbi.nlm.nih.gov/pubmed/28704270 | Daily Eating Occasions Not Reported
24 | Al Suwaidi J, Bener A, Hajar HA, Numan MT. Does hospitalization for congestive heart failure occur more frequently in Ramadan: a population-based study (1991-2001). Int J Cardiol. 2004. 96:217–21 https://www.ncbi.nlm.nih.gov/pubmed/15262036 | Intervention/Exposure, Daily Eating Occasions Not Reported
25 | Alabduljader K, Cliffe M, Sartor F, Papini G, Cox WM, Kubis HP. Ecological momentary assessment of food perceptions and eating behavior using a novel phone application in adults with or without obesity. Eat Behav. 2018. 30:35–41 https://www.ncbi.nlm.nih.gov/pubmed/29777968 | Intervention/Exposure
26 | Albertson AM, Franko DL, Thompson D, Eldridge AL, Holschuh N, Affenito SG, Bauserman R, Striegel-Moore RH. Longitudinal patterns of breakfast eating in black and white adolescent girls. Obesity. 2007. 15:2282–92 https://www.ncbi.nlm.nih.gov/pubmed/17890497 | Daily Eating Occasions Not Reported
27 | Aldhoon-Hainerova I, Hainer V, Zamrazilova H. Impact of dietary intake, lifestyle and biochemical factors on Study Design metabolic health in obese adolescents. Nutr Metab Cardiovasc Dis. 2017. 27:703–710 https://www.ncbi.nlm.nih.gov/pubmed/28693964 | Study Design
28 | Alencar MK, Beam JR, McCormick JJ, White AC, Salgado RM, Kravitz LR, Mermier CM, Gibson AL, Conn CA, Kolkmeyer D, Ferraro RT, Kerksick CM. Increased meal frequency attenuates fat-free mass losses and some markers of health status with a portion-controlled weight loss diet. Nutr Res. 2015. 35:375–83 https://www.ncbi.nlm.nih.gov/pubmed/25862614 | Eating Frequency Data Collection
29 | Alfonsson S, Sewall A, Lidholm H, Hursti T. The Meal Pattern Questionnaire: A psychometric evaluation using the Eating Disorder Examination. Eat Behav. 2016. 21:7–10 https://www.ncbi.nlm.nih.gov/pubmed/26722817 | Study Design, Outcome
30 | Alharbi TJ, Wong J, Markovic T, Yue D, Wu T, Brooks B, Hetherington J, Seimon R, Gibson AA, Toth K, Silviera S, Sainsbury A, Little TJ. Brief report: Ramadan as a model of intermittent fasting: Effects on body composition, metabolic parameters, gut hormones and appetite in adults with and without type 2 diabetes mellitus. Obesity Medicine. 2017. 6:15–17 | Daily Eating Occasions Not Reported
31 | Al-Hazzaa HM, Musaiger AO, Abahussain NA, Al-Sobayel HI, Alsulaiman NA, Tayyem RF, et al. Physical activity patterns and eating habits of adolescents living in major Arab cities. The Arab Teens Lifestyle Study. Saudi medical journal. 2010;31(2):210–1. https://www.ncbi.nlm.nih.gov/pubmed/20174744. | Study Design
32 | Al-Hourani HM, Atoum MF. Body composition, nutrient intake and physical activity patterns in young women during Ramadan. Singapore Med J. 2007. 48:906–10 https://www.ncbi.nlm.nih.gov/pubmed/17909674 | Daily Eating Occasions Not Reported
33 | Alhussain M, Macdonald IA, Taylor MA. Deleterious effects of irregular meal pattern on dietary thermogenesis in obese women. Proceedings of the nutrition society. 2016. 75:E6 | Study Design, Publication Status
34 | Alhussain M, Taylor MA, MacDonald IA. Influence of the constancy of daily meal pattern on postprandial energy expenditure in healthy weight women. Proceedings of the nutrition society. 2015. 74: OCE1 | Study Design, Publication Status
35 | Alhussain MH, Macdonald IA, Taylor MA. Irregular meal-pattern effects on energy expenditure, metabolism, and appetite regulation: a randomized controlled trial in healthy normal-weight women. Am J Clin Nutr. 2016. 104:21–32 https://www.ncbi.nlm.nih.gov/pubmed/27305952 | Eating Frequency Data Collection
36 | Ali Z, Abizari AR. Ramadan fasting alters food patterns, dietary diversity and body weight among Ghanaian adolescents. Nutr J. 2018. 17:75 https://www.ncbi.nlm.nih.gov/pubmed/30098591 | Daily Eating Occasions Not Reported, Country
37 | Alken J, Petriczko E, Marcus C. Effect of fasting on young adults who have symptoms of hypoglycemia in the absence of frequent meals. Eur J Clin Nutr. 2008. 62:721–6 https://www.ncbi.nlm.nih.gov/pubmed/17522614 | Intervention/Exposure, Daily Eating Occasions Not Reported, Comparator
38 | Alleman RJ, Harvey IC, Farney TM, Bloomer RJ. Both a traditional and modified Daniel Fast improve the cardiometabolic profile in men and women. Lipids Health Dis. 2013. 12:114 https://www.ncbi.nlm.nih.gov/pubmed/23889755 | Comparator, Size of Study Groups
39 | Allerton DM, Campbell MD, Gonzalez JT, West DJ, Stevenson EJ. The effect of breakfast macronutrient content or skipping breakfast on 24h glucose profiles. Diabetic medicine. 2015. 32:55 (Suppl.1) | Publication Status
40 | Allirot X, Saulais L, Seyssel K, Graeppi-Dulac J, Roth H, Charrie A, Drai J, Goudable J, Blond E, Disse E, Laville M. An isocaloric increase of eating episodes in the morning contributes to decrease energy intake at lunch in lean men. Physiol Behav. 2013. 110-111:169–78 https://www.ncbi.nlm.nih.gov/pubmed/23333553 | Daily Eating Occasions Not Reported
41 | Allirot X, Seyssel K, Saulais L, Roth H, Charrie A, Drai J, Goudable J, Blond E, Disse E, Laville M. Effects of a breakfast spread out over time on the food intake at lunch and the hormonal responses in obese men. Physiol Behav. 2014. 127:37–44 https://www.ncbi.nlm.nih.gov/pubmed/24472321 | Daily Eating Occasions Not Reported
42 | Allison KC, Ahima RS, O’Reardon JP, Dinges DF, Sharma V, Cummings DE, Heo M, Martino NS, Stunkard AJ. Neuroendocrine profiles associated with energy intake, sleep, and stress in the night eating syndrome. J Clin Endocrinol Metab. 2005. 90:6214–7 https://www.ncbi.nlm.nih.gov/pubmed/16131578 | Study Design, Intervention/Exposure, Daily Eating Occasions Not Reported
43 | Almeneessier AS, Bahammam AS, Sharif MM, Bahammam SA, Nashwan SZ, Pandi Perumal SR, Cardinali DP, Alzoghaibi M. The influence of intermittent fasting on the circadian pattern of melatonin while controlling for caloric intake, energy expenditure, light exposure, and sleep schedules: A preliminary report. Ann Thorac Med. 2017. 12:183–190 https://www.ncbi.nlm.nih.gov/pubmed/28808490 | Daily Eating Occasions Not Reported, Outcome, Size of Study Groups
44 | Almoosawi S, Prynne CJ, Hardy R, Stephen AM. Diurnal eating rhythms: association with long-term development of diabetes in the 1946 British birth cohort. Nutr Metab Cardiovasc Dis. 2013. 23:1025–30 https://www.ncbi.nlm.nih.gov/pubmed/23541169 | Intervention/Exposure
45 | Almoosawi S, Prynne CJ, Hardy R, Stephen AM. Time-of-day and nutrient composition of eating occasions: prospective association with the metabolic syndrome in the 1946 British birth cohort. Int J Obes (Lond). 2013. 37:725–31 https://www.ncbi.nlm.nih.gov/pubmed/22777542 | Intervention/Exposure, Daily Eating Occasions Not Reported
46 | Aloui A, Chaouachi A, Chtourou H, Wong del P, Haddad M, Chamari K, Souissi N. Effects of Ramadan on the diurnal variations of repeated-sprint performances. Int J Sports Physiol Perform. 2013. 8:254–62 https://www.ncbi.nlm.nih.gov/pubmed/22952200 | Daily Eating Occasions Not Reported, Outcome
47 | Al-Ozairi E, Al Kandari J, AlHaqqan D, AlHarbi O, Masters Y, Syed AA. Obesity surgery and Ramadan: a prospective analysis of nutritional intake, hunger and satiety and adaptive behaviours during fasting. Obes Surg. 2015. 25:523–9 https://www.ncbi.nlm.nih.gov/pubmed/25595382 | Health Status
48 | Al-Shafei AI. Ramadan fasting ameliorates arterial pulse pressure and lipid profile, and alleviates oxidative stress in hypertensive patients. Blood Press. 2014. 23:160–7 https://www.ncbi.nlm.nih.gov/pubmed/24059637 | Intervention/Exposure, Daily Eating Occasions Not Reported
49 | Alsharairi NA, Somerset SM. Skipping breakfast in early childhood and its associations with maternal and child BMI: a study of 2-5-year-old Australian children. Eur J Clin Nutr. 2016. 70:450–5 https://www.ncbi.nlm.nih.gov/pubmed/26508462 | Daily Eating Occasions Not Reported
50 | Alsubheen SA, Ismail M, Baker A, Blair J, Adebayo A, Kelly L, Chandurkar V, Cheema S, Joanisse DR, Basset FA. The effects of diurnal Ramadan fasting on energy expenditure and substrate oxidation in healthy men. Br J Nutr. 2017. 118:1023–1030 https://www.ncbi.nlm.nih.gov/pubmed/29198194 | Daily Eating Occasions Not Reported
51 | Alwasel SH, Abotalib Z, Aljarallah JS, Osmond C, Alkharaz SM, Alhazza IM, Harrath A, Thornburg K, Barker DJ. Sex differences in birth size and intergenerational effects of intrauterine exposure to Ramadan in Saudi Arabia. Am J Hum Biol. 2011. 23:651–4 https://www.ncbi.nlm.nih.gov/pubmed/21630372 | Daily Eating Occasions Not Reported, Outcome
52 | Alwasel SH, Harrath A, Aljarallah JS, Abotalib Z, Osmond C, Al Omar SY, Khaled I, Barker DJ. Intergenerational effects of in utero exposure to Ramadan in Tunisia. Am J Hum Biol. 2013. 25:341–3 https://www.ncbi.nlm.nih.gov/pubmed/23436278 | Daily Eating Occasions Not Reported, Outcome
53 | Alwattar AY, Thyfault JP, Leidy HJ. The effect of breakfast type and frequency of consumption on glycemic response in overweight/obese late adolescent girls. Eur J Clin Nutr. 2015. 69:885–90 https://www.ncbi.nlm.nih.gov/pubmed/25711955 | Intervention/Exposure, Daily Eating Occasions Not Reported
54 | Amigo-Vazquez I, Busto-Zapico R, Errasti-Perez JM, Pena-Suarez E. Skipping breakfast, sedentarism and overweight in children. Psychol Health Med. 2016. 21:819–26 https://www.ncbi.nlm.nih.gov/pubmed/26728102 | Study Design, Daily Eating Occasions Not Reported
55 | Ammerman A, Leung MM, Cavallo D. Addressing disparities in the obesity epidemic. N C Med J. 2006. 67:301–4 https://www.ncbi.nlm.nih.gov/pubmed/17066662 | Intervention/Exposure
56 | Amodio D, D’Amico M, Meret L, Gaizo A, Laviano A. Time restricted feeding (TRF) enhances weight loss efficiency in dietary restricted women with metabolic syndrome. Clinical nutrition. 2016. 35:S39– | Study Design, Publication Status
57 | Amosa T, Rush E, Plank L. Frequency of eating occasions reported by young New Zealand Polynesian and European women. Pac Health Dialog. 2001. 8:59–65 https://www.ncbi.nlm.nih.gov/pubmed/12017838 | Study Design
58 | Andersen AE, Klinger D. The overeater self and the healthy self within. Eating Disorders. 2002. 10:87–91 | Study Design
59 | Andersen GS, Stunkard AJ, Sorensen TI, Petersen L, Heitmann BL. Night eating and weight change in middle-aged Intervention/Exposure, Daily men and women. Int J Obes Relat Metab Disord. 2004. 28:1338–43 https://www.ncbi.nlm.nih.gov/pubmed/15278102 | Eating Occasions Not Reported
60 | Anderson YC, Wynter LE, Butler MS, Grant CC, Stewart JM, Cave TL, Wild CE, Derraik JG, Cutfield WS, Hofman PL. Dietary Intake and Eating Behaviours of Obese New Zealand Children and Adolescents Enrolled in a Community-Based Intervention Programme. PLoS One. 2016. 11:e0166996 https://www.ncbi.nlm.nih.gov/pubmed/27880804 | Intervention/Exposure, Daily Eating Occasions Not Reported
61 | Andersson I, Lennernas M, Rossner S. Meal pattern and risk factor evaluation in one-year completers of a weight reduction program for obese men - the ‘Gustaf’ study. J Intern Med. 2000. 247:30–8 https://www.ncbi.nlm.nih.gov/pubmed/10672128 | Outcome
62 | Androutsos O, Moschonis G, Mavrogianni C, Roma-Giannikou E, Chrousos GP, Kanaka-Gantenbein C, Manios Y. Identification of lifestyle patterns, including sleep deprivation, associated with insulin resistance in children: the Healthy Growth Study. Eur J Clin Nutr. 2014. 68:344–9 https://www.ncbi.nlm.nih.gov/pubmed/24424081 | Study Design
63 | Anton SD, Lee SA, Donahoo WT, McLaren C, Manini T, Leeuwenburgh C, et al. The Effects of Time Restricted Feeding on Overweight, Older Adults: A Pilot Study. Nutrients. 2019;11(7). https://www.ncbi.nlm.nih.gov/pubmed/31262054. | Daily Eating Occasions Not Reported
64 | Antoni R, Johnston K, Collins A, Robertson M. The comparative effects of intermittent versus continuous energy restriction on postprandial glucose and lipid metabolism following 5% weight-loss. Obesity facts. 2017. 10:S209 | Publication Status
65 | Antoni R, Johnston KL, Collins A, Robertson MD. Investigation into the acute effects of intermittent energy restriction on postprandial substrate metabolism. Proceedings of the nutrition society. 2016. 75:E29 | Study Design, Publication Status
66 | Antoni R, Johnston KL, Collins AL, Robertson MD. Acute effects of intermittent energy restriction on energy compensation: a pilot study. Obesity facts. 2015. 8:76 | Publication Status
67 | Antoni R, Johnston KL, Collins AL, Robertson MD. Intermittent v. continuous energy restriction: differential effects on postprandial glucose and lipid metabolism following matched weight loss in overweight/obese participants. Br J Nutr. 2018. 119:507–516 https://www.ncbi.nlm.nih.gov/pubmed/29508693 | Daily Eating Occasions Not Reported, Size of Study Groups
68 | Antoni R, Johnston KL, Collins AL, Robertson MD. Investigation into the acute effects of total and partial energy restriction on postprandial metabolism among overweight/obese participants. Br J Nutr. 2016. 115:951–9 https://www.ncbi.nlm.nih.gov/pubmed/26819200 | Intervention/Exposure, Daily Eating Occasions Not Reported
69 | Antoni R, Johnston KL, Collins AL, Robertson MD. The comparative effects of intermittent versus continuous energy restriction on postprandial glucose-lipid metabolism following 5 % weight-loss: interim analysis of an ongoing study. Proceedings of the nutrition society. 2016. 75:E105 | Publication Status
70 | Aparicio A, Rodriguez-Rodriguez E, Aranceta-Bartrina J, Gil A, Gonzalez-Gross M, Serra-Majem L, Varela-Moreiras G, Ortega RM. Differences in meal patterns and timing with regard to central obesity in the ANIBES (‘Anthropometric data, macronutrients and micronutrients intake, practice of physical activity, socioeconomic data and lifestyles in Spain’) Study - CORRIGENDUM. Public Health Nutr. 2018. 21:1588 https://www.ncbi.nlm.nih.gov/pubmed/29506590 | Publication Status
71 | Appleton KM, Baker S. Distraction, not hunger, is associated with lower mood and lower perceived work performance on fast compared to non-fast days during intermittent fasting. J Health Psychol. 2015. 20:702–11 https://www.ncbi.nlm.nih.gov/pubmed/26032787 | Intervention/Exposure, Daily Eating Occasions Not Reported, Outcome
72 | Arciero PJ, Ormsbee MJ, Gentile CL, Nindl BC, Brestoff JR, Ruby M. Increased protein intake and meal frequency reduces abdominal fat during energy balance and energy deficit. Obesity (Silver Spring). 2013. 21:1357–66 https://www.ncbi.nlm.nih.gov/pubmed/23703835 | Size of Study Groups
73 | Arguin H, Dionne IJ, Senechal M, Bouchard DR, Carpentier AC, Ardilouze JL, Tremblay A, Leblanc C, Brochu M. Short- and long-term effects of continuous versus intermittent restrictive diet approaches on body composition and the metabolic profile in overweight and obese postmenopausal women: a pilot study. Menopause. 2012. 19:870–6 https://www.ncbi.nlm.nih.gov/pubmed/22735163 | Daily Eating Occasions Not Reported
74 | Aronoff NJ, Geliebter A, Zammit G. Gender and body mass index as related to the night-eating syndrome in obese outpatients. J Am Diet Assoc. 2001. 101:102–4 https://www.ncbi.nlm.nih.gov/pubmed/11209573 | Intervention/Exposure, Daily Eating Occasions Not Reported
75 | Asarnow LD, Greer SM, Walker MP, Harvey AG. The Impact of Sleep Improvement on Food Choices in Adolescents With Late Bedtimes. J Adolesc Health. 2017. 60:570–576 https://www.ncbi.nlm.nih.gov/pubmed/28111011 | Intervention/Exposure
76 | Asci O, Rathfisch G. Effect of lifestyle interventions of pregnant women on their dietary habits, lifestyle behaviors, and weight gain: a randomized controlled trial. J Health Popul Nutr. 2016. 35:7 https://www.ncbi.nlm.nih.gov/pubmed/26911204 | Daily Eating Occasions Not Reported
77 | Ask AS, Hernes S, Aarek I, Johannessen G, Haugen M. Changes in dietary pattern in 15 year old adolescents following a 4 month dietary intervention with school breakfast--a pilot study. Nutr J. 2006;5:33. https://www.ncbi.nlm.nih.gov/pubmed/17150115. | Intervention/Exposure, Daily Eating Occasions Not Reported
78 | Ask AS, Hernes S, Aarek I, Johannessen G, Haugen M. Changes in dietary pattern in 15 year old adolescents following a 4 month dietary intervention with school breakfast—a pilot study. Nutr J. 2006. 5:33 https://www.ncbi.nlm.nih.gov/pubmed/17150115 | Daily Eating Occasions Not Reported
79 | Askari VR, Alavinezhad A, Boskabady MH. The impact of Ramadan fasting period on total and differential white blood cells, haematological indices, inflammatory biomarker, respiratory symptoms and pulmonary function tests of healthy and asthmatic patients. Allergologia et Immunopathologia. 2016;44(4):359–67. https://www.ncbi.nlm.nih.gov/pubmed/27040808. | Daily Eating Occasions Not Reported
80 | Assadi M, Akrami A, Beikzadeh F, Seyedabadi M, Nabipour I, Larijani B, Afarid M, Seidali E. Impact of Ramadan fasting on intraocular pressure, visual acuity and refractive errors. Singapore Med J. 2011. 52:263–6 https://www.ncbi.nlm.nih.gov/pubmed/21552787 | Daily Eating Occasions Not Reported, Outcome
81 | Astbury NM, Taylor MA, Macdonald IA. Breakfast consumption affects appetite, energy intake, and the metabolic and endocrine responses to foods consumed later in the day in male habitual breakfast eaters. J Nutr. 2011. 141:1381–9 https://www.ncbi.nlm.nih.gov/pubmed/21562233 | Daily Eating Occasions Not Reported, Outcome
82 | Azizi F. Islamic fasting and health. Annals of nutrition & metabolism. 2010;56(4):273–82. https://www.ncbi.nlm.nih.gov/pubmed/20424438. | Study Design
83 | Bachman J, Raynor H. Does eating more frequently increase weight loss during a behavioral weight loss intervention?. Obesity (silver spring, md.). 2011. 19:S61–S62 https://www.cochranelibrary.com/central/doi/10.1002/central/CN-01005798/full | Publication Status
84 | Bachman JL, Phelan S, Wing RR, Raynor HA. Eating frequency is higher in weight loss maintainers and normal-weight individuals than in overweight individuals. J Am Diet Assoc. 2011. 111:1730–4 https://www.ncbi.nlm.nih.gov/pubmed/22027056 | Study Design
85 | BaHammam A, Alrajeh M, Albabtain M, Bahammam S, Sharif M. Circadian pattern of sleep, energy expenditure, and body temperature of young healthy men during the intermittent fasting of Ramadan. Appetite. 2010;54(2):426–9. https://www.ncbi.nlm.nih.gov/pubmed/20100529. | Daily Eating Occasions Not Reported
86 | Bahammam AS, Almushailhi K, Pandi-Perumal SR, Sharif MM. Intermittent fasting during Ramadan: does it affect sleep?. J Sleep Res. 2014. 23:35–43 https://www.ncbi.nlm.nih.gov/pubmed/23937329 | Daily Eating Occasions Not Reported
87 | Bahammam AS, Nashwan S, Hammad O, Sharif MM, Pandi-Perumal SR. Objective assessment of drowsiness and reaction time during intermittent Ramadan fasting in young men: a case-crossover study. Behav Brain Funct. 2013. 9:32 https://www.ncbi.nlm.nih.gov/pubmed/23937904 | Intervention/Exposure, Daily Eating Occasions Not Reported
88 | BaHammam AS, Pandi-Perumal SR, Alzoghaibi MA. The effect of Ramadan intermittent fasting on lipid peroxidation in healthy young men while controlling for diet and sleep: A pilot study. Ann Thorac Med. 2016. 11:43–8 https://www.ncbi.nlm.nih.gov/pubmed/26933456 | Daily Eating Occasions Not Reported
89 | Bahijri S, Borai A, Ajabnoor G, Abdul Khaliq A, AlQassas I, Al-Shehri D, Chrousos G. Relative metabolic stability, but disrupted circadian cortisol secretion during the fasting month of Ramadan. PLoS One. 2013. 8:e60917 https://www.ncbi.nlm.nih.gov/pubmed/23637777 | Intervention/Exposure, Daily Eating Occasions Not Reported
90 | Bak AM, Vendelbo MH, Christensen B, Viggers R, Bibby BM, Rungby J, Jorgensen JOL, Moller N, Jessen N. Prolonged fasting-induced metabolic signatures in human skeletal muscle of lean and obese men. PLoS One. 2018. 13:e0200817 https://www.ncbi.nlm.nih.gov/pubmed/30183740 | Intervention/Exposure, Daily Eating Occasions Not Reported
91 | Bakan AA, Yildiz S, Alkan A, Yetis H, Kurtcan S, Ilhan MM. Microstructural effects of Ramadan fasting on the brain: a diffusion tensor imaging study. Diagn Interv Radiol. 2015. 21:256–61 https://www.ncbi.nlm.nih.gov/pubmed/25835077 | Intervention/Exposure, Daily Eating Occasions Not Reported, Outcome
92 | Balieiro LC, Rossato LT, Waterhouse J, Paim SL, Mota MC, Crispim CA. Nutritional status and eating habits of bus drivers during the day and night. Chronobiol Int. 2014. 31:1123–9 https://www.ncbi.nlm.nih.gov/pubmed/25231504 | Study Design
93 | Barba G, Troiano E, Russo P, Siani A. Total fat, fat distribution and blood pressure according to eating frequency in children living in southern Italy: the ARCA project. Int J Obes (Lond). 2006. 30:1166–9 https://www.ncbi.nlm.nih.gov/pubmed/16462817 | Study Design
94 | Barkia A, Mohamed K, Smaoui M, Zouari N, Hammami M, Nasri M. Change of diet, plasma lipids, lipoproteins, and fatty acids during Ramadan: a controversial association of the considered Ramadan model with atherosclerosis risk. J Health Popul Nutr. 2011. 29:486–93 https://www.ncbi.nlm.nih.gov/pubmed/22106754 | Daily Eating Occasions Not Reported
95 | Barnosky A, Kroeger CM, Trepanowski JF, Klempel MC, Bhutani S, Hoddy KK, Gabel K, Shapses SA, Varady KA. Effect of alternate day fasting on markers of bone metabolism: An exploratory analysis of a 6-month randomized controlled trial. Nutr Healthy Aging. 2017. 4:255–263 https://www.ncbi.nlm.nih.gov/pubmed/29276795 | Daily Eating Occasions Not Reported, Size of Study Groups
96 | Baron KG, Reid KJ, Kern AS, Zee PC. Role of sleep timing in caloric intake and BMI. Obesity (Silver Spring). 2011. 19:1374–81 https://www.ncbi.nlm.nih.gov/pubmed/21527892 | Study Design, Daily Eating Occasions Not Reported
97 | Baron KG, Reid KJ, Kim T, Van Horn L, Attarian H, Wolfe L, Siddique J, Santostasi G, Zee PC. Circadian timing and alignment in healthy adults: associations with BMI, body fat, caloric intake and physical activity. Int J Obes (Lond). 2017. 41:203–209 https://www.ncbi.nlm.nih.gov/pubmed/27795550 | Intervention/Exposure
98 | Basilakis A, Kiprouli K, Mantzouranis S, Konstantinidis T, Dionisopoulou M, Hackl JM, Balogh D. Nutritional study in Greek-Orthodox monasteries - Effect of a 40-day religious fasting. Aktuelle Ernahrungsmedizin. 2002. 27:250–255 | Study Design, Intervention/Exposure, Daily Eating Occasions Not Reported
99 | Bataineh MF, Al-Nawaiseh AM, Abu Altaieb MH, Bellar DM, Hindawi OS, Judge LW. Impact of carbohydrate mouth rinsing on time to exhaustion during Ramadan: A randomized controlled trial in Jordanian men. Eur J Sport Sci. 2018. 18:357–366 https://www.ncbi.nlm.nih.gov/pubmed/29364063 | Intervention/Exposure
100 | Batista-Jorge GC, Barcala-Jorge AS, Oliveira Dias AF, Silveira MF, de Farias Lelis D, Oliveira Andrade JM, Claro RM, de Paula AM, Guimaraes AL, Ferreira AV, Santos SH. Nutritional Status Associated to Skipping Breakfast in Brazilian Health Service Patients. Ann Nutr Metab. 2016. 69:31–40 https://www.ncbi.nlm.nih.gov/pubmed/27434543 | Study Design
101 | Baum JI, Gaines BL, Kubas GC, Mitchell CF, Russell SL. Educational nutrition messaging at breakfast reduces snack intake and influences snack preferences in adult men and women. Appetite. 2017. 117:67–73 https://www.ncbi.nlm.nih.gov/pubmed/28627401 | Intervention/Exposure, Daily Eating Occasions Not Reported
102 | Baxter SD, Hardin JW, Guinn CH, Royer JA, Mackelprang AJ, Devlin CM. Children’s body mass index, participation in school meals, and observed energy intake at school meals. International journal of behavioral nutrition and physical activity. 2010;7. https://www.ncbi.nlm.nih.gov/pubmed/20334667. | Intervention/Exposure, Daily Eating Occasions Not Reported
103 | Beebe D, Chang JJ, Kress K, Mattfeldt-Beman M. Diet quality and sleep quality among day and night shift nurses. J Nurs Manag. 2017. 25:549–557 https://www.ncbi.nlm.nih.gov/pubmed/28695685 | Study Design, Comparator, Outcome
104 | Beer A-M, Ismar LE, Wessely DK, Pötschke T, Weidner B, Wiebelitz KR. Retrospective Long-Term Comparison of Naturopathic Fasting Therapy and Weight Reduction Diet in Overweight Patients. Evidence-based Complementary & Alternative Medicine (eCAM). 2014;2014:1–8. https://www.ncbi.nlm.nih.gov/pubmed/25126098. | Intervention/Exposure, Daily Eating Occasions Not Reported
105 | Befort CA, Stewart EE, Smith BK, Gibson CA, Sullivan DK, Donnelly JE. Weight maintenance, behaviors and barriers among previous participants of a university-based weight control program. Int J Obes (Lond). 2008. 32:519–26 https://www.ncbi.nlm.nih.gov/pubmed/18059404 | Study Design
106 | Bekersky I, Dressler D, Mekki Q. Effect of time of meal consumption on bioavailability of a single oral 5 mg tacrolimus dose. J Clin Pharmacol. 2001. 41:289–97 https://www.ncbi.nlm.nih.gov/pubmed/11269569 | Intervention/Exposure, Outcome
107 | Bellisle F, Dalix AM, Mennen L, Galan P, Hercberg S, de Castro JM, Gausseres N. Contribution of snacks and meals in the diet of French adults: a diet-diary study. Physiol Behav. 2003. 79:183–9 https://www.ncbi.nlm.nih.gov/pubmed/12834789 | Outcome
108 | Benchekroun MT, Moussamih S. Effects of Ramadan fasting on cardiovascular diseases. Saudi Med J. 2004. 25:1520–1 https://www.ncbi.nlm.nih.gov/pubmed/15494846 | Study Design
109 | Bener A, Hamad A, Fares A, Al-Sayed HM, Al-Suwaidi J. Is there any effect of Ramadan fasting on stroke incidence?. Singapore Med J. 2006. 47:404–8 https://www.ncbi.nlm.nih.gov/pubmed/16645691 | Intervention/Exposure, Daily Eating Occasions Not Reported
110 | Berg C, Lappas G, Wolk A, Strandhagen E, Toren K, Rosengren A, Thelle D, Lissner L. Eating patterns and portion size associated with obesity in a Swedish population. Appetite. 2009. 52:21–6 https://www.ncbi.nlm.nih.gov/pubmed/18694791 | Study Design
111 | Berge JM, Wall M, Larson N, Loth KA, Neumark-Sztainer D. Family functioning: associations with weight status, eating behaviors, and physical activity in adolescents. J Adolesc Health. 2013. 52:351–7 https://www.ncbi.nlm.nih.gov/pubmed/23299010 | Study Design
112 | Berkey CS, Rockett HR, Gillman MW, Field AE, Colditz GA. Longitudinal study of skipping breakfast and weight change in adolescents. Int J Obes Relat Metab Disord. 2003. 27:1258–66 https://www.ncbi.nlm.nih.gov/pubmed/14513075 | Daily Eating Occasions Not Reported
113 | Bernardo LM, Stein H, Flavin PM. The ABCDiet program: evaluation of project outcomes. School Nurse News. 2010. 27:16–9 https://www.ncbi.nlm.nih.gov/pubmed/20945675 | Study Design, Publication Status
114 | Bernice Dodor. The Impact of Religiosity on Health Behaviors and Obesity among African Americans. Journal of Human Behavior in the Social Environment. 2012. 22:451–462 | Intervention/Exposure
115 | Berteus Forslund H, Klingstrom S, Hagberg H, Londahl M, Torgerson JS, Lindroos AK. Should snacks be recommended in obesity treatment? A 1-year randomized clinical trial. Eur J Clin Nutr. 2008. 62:1308–17 https://www.ncbi.nlm.nih.gov/pubmed/17700649 | Eating Frequency Data Collection
116 | Bertz F, Sparud-Lundin C, Winkvist A. Transformative Lifestyle Change: key to sustainable weight loss among women in a post-partum diet and exercise intervention. Matern Child Nutr. 2015. 11:631–45 https://www.ncbi.nlm.nih.gov/pubmed/24750689 | Intervention/Exposure
117 | Bes-Rastrollo M, Sanchez-Villegas A, Basterra-Gortari FJ, Nunez-Cordoba JM, Toledo E, Serrano-Martinez M. Prospective study of self-reported usual snacking and weight gain in a Mediterranean cohort: the SUN project. Clin Nutr. 2010. 29:323–30 https://www.ncbi.nlm.nih.gov/pubmed/19748710 | Daily Eating Occasions Not Reported
118 | Betoko A, Lioret S, Heude B, Hankard R, Carles S, Forhan A, Regnault N, Botton J, Charles MA, de Lauzon-Guillain B. Influence of infant feeding patterns over the first year of life on growth from birth to 5 years. Pediatr Obes. 2017. 12 Suppl 1:94–101 https://www.ncbi.nlm.nih.gov/pubmed/28299906 | Age: Intervention/Exposure
119 | Bhattarai MD, Singh DL. Excessive weight gain after pregnancy in urban areas: one important area to prevent diabetes. Nepal Med Coll J. 2005. 7:87–9 https://www.ncbi.nlm.nih.gov/pubmed/16519070 | Intervention/Exposure, Country
120 | Bhutani S, Klempel MC, Berger RA, Varady KA. Improvements in coronary heart disease risk indicators by alternate-day fasting involve adipose tissue modulations. Obesity (Silver Spring). 2010. 18:2152–9 https://www.ncbi.nlm.nih.gov/pubmed/20300080 | Daily Eating Occasions Not Reported
121 | Bhutani S, Klempel MC, Kroeger CM, Aggour E, Calvo Y, Trepanowski JF, Hoddy KK, Varady KA. Effect of exercising while fasting on eating behaviors and food intake. J Int Soc Sports Nutr. 2013. 10:50 https://www.ncbi.nlm.nih.gov/pubmed/24176020 | Intervention/Exposure, Daily Eating Occasions Not Reported
122 | Bhutani S, Klempel MC, Kroeger CM, Trepanowski JF, Phillips SA, Norkeviciute E, Varady KA. Alternate day fasting with or without exercise: effects on endothelial function and adipokines in obese humans. E-spen journal. 2013. 8:e205–e209 | Daily Eating Occasions Not Reported
123 | Bhutani S, Klempel MC, Kroeger CM, Trepanowski JF, Varady KA. Alternate day fasting and endurance exercise combine to reduce body weight and favorably alter plasma lipids in obese humans. Obesity (Silver Spring). 2013. 21:1370–9 https://www.ncbi.nlm.nih.gov/pubmed/23408502 | Daily Eating Occasions Not Reported
124 | Bhutani S, Klempel MC, Kroeger CM, Varady KA. Combining alternate day fasting with exercise improves plasma lipids and ldl particle size in obese humans. Clinical nutrition, supplement. 2012. 7:10–11 | Study Design, Publication Status
125 | Bhutani S, Klempel MC, Kroeger CM, Varady KA. OP024 Combining alternate day fasting with exercise improves plasma lipids and ldl particle size in obese humans. Clinical Nutrition Supplements. 2012. 7:10–11 | Study Design, Publication Status
126 | Bhutani S, Varady KA, Klempel MC, Kroeger CM. Alternate day fasting combined with exercise: an effective treatment for weight loss and cardio-protection in obese humans. FASEB journal. 2012;26. | Study Design, Publication Status
127 | Bjornshave A, Holst JJ, Hermansen K. A pre-meal of whey proteins induces differential effects on glucose and lipid metabolism in subjects with the metabolic syndrome: a randomised cross-over trial. Eur J Nutr. 2019. 58:755–764 https://www.ncbi.nlm.nih.gov/pubmed/29626232 | Intervention/Exposure
128 | Bloomgarden ZT. Prevention of cardiovascular disease. Diabetes care. 2007. 30:423–431 https://www.cochranelibrary.com/central/doi/10.1002/central/CN-01721552/full | Study Design, Intervention/Exposure
129 | Bo S, De Carli L, Venco E, Fanzola I, Maiandi M, De Michieli F, Durazzo M, Beccuti G, Cavallo-Perin P, Ghigo E, Ganzit GP. Impact of snacking pattern on overweight and obesity risk in a cohort of 11- to 13-year-old adolescents. J Pediatr Gastroenterol Nutr. 2014. 59:465–71 https://www.ncbi.nlm.nih.gov/pubmed/24897170 | Study Design
130 | Bo S, Fadda M, Castiglione A, Ciccone G, De Francesco A, Fedele D, Guggino A, Parasiliti Caprino M, Ferrara S, Vezio Boggio M, Mengozzi G, Ghigo E, Maccario M, Broglio F. Is the timing of caloric intake associated with variation in diet-induced thermogenesis and in the metabolic pattern? A randomized cross-over study. Int J Obes (Lond). 2015. 39:1689–95 https://www.ncbi.nlm.nih.gov/pubmed/26219416 | Intervention/Exposure, Daily Eating Occasions Not Reported, Comparator
131 | Bocca G, Kuitert MWB, Sauer PJJ, Corpeleijn E. Effect of a multidisciplinary treatment program on eating behavior in overweight and obese preschool children. J Pediatr Endocrinol Metab. 2018. 31:507–513 https://www.ncbi.nlm.nih.gov/pubmed/29652666 | Intervention/Exposure, Outcome
132 | Boonchoo W, Takemi Y, Hayashi F, Koiwai K, Ogata H. Dietary intake and weight status of urban Thai preadolescents in the context of food environment. Prev Med Rep. 2017. 8:153–157 https://www.ncbi.nlm.nih.gov/pubmed/29881667 | Study Design
133 | Booth DA, Blair AJ, Lewis VJ, Baek SH. Patterns of eating and movement that best maintain reduction in overweight. Appetite. 2004. 43:277–83 https://www.ncbi.nlm.nih.gov/pubmed/15527930 | Study Design, Intervention/Exposure, Daily Eating Occasions Not Reported
134 | Borzecki A, Zolkowska D, Sieklucka-Dziuba M. Life style and the risk of development of circulatory system diseases. Ann Univ Mariae Curie Sklodowska Med. 2002. 57:426–32 https://www.ncbi.nlm.nih.gov/pubmed/12898955 | Study Design
135 | Boston RC, Moate PJ, Allison KC, Lundgren JD, Stunkard AJ. Modeling circadian rhythms of food intake by means of parametric deconvolution: results from studies of the night eating syndrome. Am J Clin Nutr. 2008. 87:1672–7 https://www.ncbi.nlm.nih.gov/pubmed/18541555 | Study Design, Intervention/Exposure, Daily Eating Occasions Not Reported
136 | Bouhlel E, Denguezli M, Zaouali M, Tabka Z, Shephard RJ. Ramadan fastings effect on plasma leptin, adiponectin concentrations, and body composition in trained young men. Int J Sport Nutr Exerc Metab. 2008. 18:617–27 https://www.ncbi.nlm.nih.gov/pubmed/19164831 | Intervention/Exposure, Daily Eating Occasions Not Reported
137 | Bouhlel E, Salhi Z, Bouhlel H, Mdella S, Amamou A, Zaouali M, Mercier J, Bigard X, Tabka Z, Zbidi A, Shephard RJ. Effect of Ramadan fasting on fuel oxidation during exercise in trained male rugby players. Diabetes Metab. 2006. 32:617–24 https://www.ncbi.nlm.nih.gov/pubmed/17296516 | Intervention/Exposure, Daily Eating Occasions Not Reported
138 | Bouhlel E, Zaouali M, Miled A, Tabka Z, Bigard X, Shephard R. Ramadan fasting and the GH/IGF-1 axis of trained men during submaximal exercise. Ann Nutr Metab. 2008. 52:261–6 https://www.ncbi.nlm.nih.gov/pubmed/18617733 | Intervention/Exposure, Daily Eating Occasions Not Reported
139 | Bouhlel H, Shephard RJ, Gmada N, Aouichaoui C, Peres G, Tabka Z, Bouhlel E. Effect of Ramadan observance on maximal muscular performance of trained men. Clin J Sport Med. 2013. 23:222–7 https://www.ncbi.nlm.nih.gov/pubmed/23160275 | Intervention/Exposure, Daily Eating Occasions Not Reported, Outcome
140 | Bouida W, Beltaief K, Baccouche H, Sassi M, Dridi Z, Trabelsi I, Laaouiti K, Chakroun T, Hellara I, Boukef R, Sakly N, Hassine M, Added F, Razgallah R, Najjar F, Nouira S. Effects of Ramadan fasting on aspirin resistance in type 2 diabetic patients. PLoS One. 2018. 13:e0192590 https://www.ncbi.nlm.nih.gov/pubmed/29529091 | Health Status
141 | Bowen J, Brindal E, James-Martin G, Noakes M. Randomized Trial of a High Protein, Partial Meal Replacement Program with or without Alternate Day Fasting: Similar Effects on Weight Loss, Retention Status, Nutritional, Metabolic, and Behavioral Outcomes. Nutrients. 2018;10(9). https://www.ncbi.nlm.nih.gov/pubmed/30142886. | Daily Eating Occasions Not Reported, Comparator
142 | Breakfast: pro and con. It’s always been billed as the most important meal of the day—until now. Duke Med Health News. 2014. 20:6–7 https://www.ncbi.nlm.nih.gov/pubmed/25481929 | Publication Status
143 | Briatore L, Andraghetti G, Cordera R. Effect of two fasting periods of different duration on ghrelin response to a mixed meal. Nutr Metab Cardiovasc Dis. 2006. 16:471–6 https://www.ncbi.nlm.nih.gov/pubmed/17015184 | Daily Eating Occasions Not Reported, Outcome
144 | Brikou D, Zannidi D, Karfopoulou E, Anastasiou CA, Yannakoulia M. Breakfast consumption and weight-loss maintenance: results from the MedWeight study. Br J Nutr. 2016. 115:2246–51 https://www.ncbi.nlm.nih.gov/pubmed/27185413 | Daily Eating Occasions Not Reported
145 | Brisswalter J, Bouhlel E, Falola JM, Abbiss CR, Vallier JM, Hausswirth C. Effects of Ramadan intermittent fasting on middle-distance running performance in well-trained runners. Clin J Sport Med. 2011. 21:422–7 https://www.ncbi.nlm.nih.gov/pubmed/21857506 | Daily Eating Occasions Not Reported, Outcome
146 | Brophy S, Cooksey R, Gravenor MB, Mistry R, Thomas N, Lyons RA, Williams R. Risk factors for childhood obesity at age 5: analysis of the millennium cohort study. BMC Public Health. 2009. 9:467 https://www.ncbi.nlm.nih.gov/pubmed/20015353 | Intervention/Exposure, Daily Eating Occasions Not Reported
147 | Bucher Della Torre S, Wild P, Dorribo V, Amati F, Danuser B. Eating Habits of Professional Firefighters: Comparison With National Guidelines and Impact Healthy Eating Promotion Program. J Occup Environ Med. 2019. 61:e183–e190 https://www.ncbi.nlm.nih.gov/pubmed/31268938 | Intervention/Exposure
148 | Burdge GC, Jones AE, Frye SM, Goodson L, Wootton SA. Effect of meal sequence on postprandial lipid, glucose and insulin responses in young men. Eur J Clin Nutr. 2003. 57:1536–44 https://www.ncbi.nlm.nih.gov/pubmed/14647218 | Daily Eating Occasions Not Reported, Size of Study Groups
149 | Buyken AE, Trauner K, Günther ALB, Kroke A, Remer T. Breakfast glycemic index affects subsequent daily energy intake in free-living healthy children. American journal of clinical nutrition. 2007;86(4):980–7. https://www.ncbi.nlm.nih.gov/pubmed/17921374. | Intervention/Exposure, Daily Eating Occasions Not Reported
150 | Buyukkurt A, Bourguignon C, Antinora C, Farquhar E, Gao X, Passarella E, Sibthorpe D, Gou K, Saury S, Beaulieu S, Storch KF, Linnaranta O. Irregular eating patterns associate with hypomanic symptoms in bipolar disorders. Nutr Neurosci. 2019. #volume#:1–12 https://www.ncbi.nlm.nih.gov/pubmed/30873919 | Outcome, Health Status
151 | Byrne N, Hills A, Salis A, King N, Wood R. Changes in total and activity energy expenditure accompanying continuous versus intermittent energy restriction: the matador study. Obesity facts. 2018. 11:93 | Publication Status
152 | Byrne N, Sainsbury A, Wood R, King N, Hills A. Intermittent energy restriction improves weight loss efficiency in obese men. Obesity reviews. 2014. 15:52 | Publication Status
153 | Byrne NM, Sainsbury A, King NA, Hills AP, Wood RE. Intermittent energy restriction improves weight loss efficiency in obese men: the MATADOR study. Int J Obes (Lond). 2018. 42:129–138 https://www.ncbi.nlm.nih.gov/pubmed/28925405 | Daily Eating Occasions Not Reported
154 | Cachelin FM, Thomas C, Vela A, Gil-Rivas V. Associations between meal patterns, binge eating, and weight for Latinas. Int J Eat Disord. 2017. 50:32–39 https://www.ncbi.nlm.nih.gov/pubmed/27436488 | Study Design
155 | Calamaro CJ, Park S, Mason TB, Marcus CL, Weaver TE, Pack A, Ratcliffe SJ. Shortened sleep duration does not predict obesity in adolescents. J Sleep Res. 2010. 19:559–66 https://www.ncbi.nlm.nih.gov/pubmed/20545836 | Daily Eating Occasions Not Reported
156 | Cameron JD, Cyr MJ, Doucet E. Increased meal frequency does not promote greater weight loss in subjects who were prescribed an 8-week equi-energetic energy-restricted diet. Br J Nutr. 2010. 103:1098–101 https://www.ncbi.nlm.nih.gov/pubmed/19943985 | Size of Study Groups
157 | Cansel M, Tasolar H, Yagmur J, Ermis N, Acikgoz N, Eyyupkoca F, Pekdemir H, Ozdemir R. The effects of Ramadan fasting on heart rate variability in healthy individuals: a prospective study. Anadolu Kardiyol Derg. 2014. 14:413–6 https://www.ncbi.nlm.nih.gov/pubmed/24901017 | Daily Eating Occasions Not Reported
158 | Capaldi ED, Owens JQ, Privitera GJ. Isocaloric meal and snack foods differentially affect eating behavior. Appetite. 2006;46(2):117–23. https://www.ncbi.nlm.nih.gov/pubmed/16442668. | Intervention/Exposure, Daily Eating Occasions Not Reported, Outcome
159 | Cardoso Chaves O, Franceschini Sdo C, Machado Rocha Ribeiro S, Ferreira Rocha Sant Ana L, Garcon de Faria C, Priore SE. Anthropometric and biochemical parameters in adolescents and their relationship with eating habits and household food availability. Nutr Hosp. 2013. 28:1352–6 https://www.ncbi.nlm.nih.gov/pubmed/23889666 | Study Design
160 | Carels RA, Young KM, Coit C, Clayton AM, Spencer A, Wagner M. Skipping meals and alcohol consumption. The regulation of energy intake and expenditure among weight loss participants. Appetite. 2008. 51:538–45 https://www.ncbi.nlm.nih.gov/pubmed/18511146 | Daily Eating Occasions Not Reported
161 | Carey J, Neher J, St Anna L. Clinical Inquiry. Do dietary choices alone alter the risk of developing metabolic syndrome?. J Fam Pract. 2013. 62:507–19 https://www.ncbi.nlm.nih.gov/pubmed/24080561 | Publication Status
162 | Carlson JA, Crespo NC, Sallis JF, Patterson RE, Elder JP. Dietary-related and physical activity-related predictors of obesity in children: a 2-year prospective study. Child Obes. 2012. 8:110–5 https://www.ncbi.nlm.nih.gov/pubmed/22799510 | Intervention/Exposure, Daily Eating Occasions Not Reported
163 | Carlson O, Martin B, Stote KS, Golden E, Maudsley S, Najjar SS, Ferrucci L, Ingram DK, Longo DL, Rumpler WV, Baer DJ, Egan J, Mattson MP. Impact of reduced meal frequency without caloric restriction on glucose regulation in healthy, normal-weight middle-aged men and women. Metabolism. 2007. 56:1729–34 https://www.ncbi.nlm.nih.gov/pubmed/17998028 | Eating Frequency Data Collection
164 | Carrard I, Rothen S. Factors associated with disordered eating behaviors and attitudes in older women. Eat Weight Disord. 2019;1–9. https://www.ncbi.nlm.nih.gov/pubmed/30734223 | Study Design, Intervention/Exposure
165 | Cassimos D, Sidiropoulos H, Batzios S, Balodima V, Christoforidis A. Sociodemographic and dietary risk factors for excess weight in a greek pediatric population living in Kavala, Northern Greece. Nutr Clin Pract. 2011. 26:186–91 https://www.ncbi.nlm.nih.gov/pubmed/21447773 | Study Design
166 | Catenacci VA, Pan Z, Ostendorf D, Brannon S, Gozansky WS, Mattson MP, Martin B, MacLean PS, Melanson EL, Troy Donahoo W. A randomized pilot study comparing zero-calorie alternate-day fasting to daily caloric restriction in adults with obesity. Obesity (Silver Spring). 2016. 24:1874–83 https://www.ncbi.nlm.nih.gov/pubmed/27569118 | Daily Eating Occasions Not Reported, Comparator
167 | Cayres SU, Urban JB, Fernandes RA. Physical Activity and Skipping Breakfast Have Independent Effects on Body Fatness Among Adolescents. J Pediatr Gastroenterol Nutr. 2018. 67:666–670 https://www.ncbi.nlm.nih.gov/pubmed/29952827 | Daily Eating Occasions Not Reported
168 | Ccps Janovsky, Laurinavicius A, Cesena F, Valente V, Ferreira CE, Mangueira C, Conceicao R, Santos RD, Bittencourt MS. Impact of self-reported fasting duration on lipid profile variability, cardiovascular risk stratification and metabolic syndrome diagnosis. Arch Endocrinol Metab. 2018. 62:187–192 https://www.ncbi.nlm.nih.gov/pubmed/29641736 | Daily Eating Occasions Not Reported
169 | Celik A, Saricicek E, Saricicek V, Sahin E, Ozdemir G, Bozkurt S, Okumus M, Sucakli MH, Cikim G, Coskun Y, Deniz MS, Dogan E, Kilinc M. Effect of Ramadan fasting on serum concentration of apelin-13 and new obesity indices in healthy adult men. Med Sci Monit. 2014. 20:337–42 https://www.ncbi.nlm.nih.gov/pubmed/24576923 | Daily Eating Occasions Not Reported
170 | Cespedes EM, Hu FB, Redline S, Rosner B, Gillman MW, Rifas-Shiman SL, Taveras EM. Chronic insufficient sleep and diet quality: Contributors to childhood obesity. Obesity (Silver Spring). 2016. 24:184–90 https://www.ncbi.nlm.nih.gov/pubmed/26592489 | Intervention/Exposure
171 | Cha E, Talman MS, Massey AH, Yan F, Rogers AE. Sleep, Lifestyle Behaviors, and Cardiometabolic Health Markers in Overweight/Obese Young Adults: A Pilot Study Using the SenseWear® Armband. Biol Res Nurs. 2018. 20:541–548 https://www.ncbi.nlm.nih.gov/pubmed/30071743 | Study Design
172 | Chan JL, Bullen J, Lee JH, Yiannakouris N, Mantzoros CS. Ghrelin levels are not regulated by recombinant leptin administration and/or three days of fasting in healthy subjects. J Clin Endocrinol Metab. 2004. 89:335–43 https://www.ncbi.nlm.nih.gov/pubmed/14715869 | Intervention/Exposure, Daily Eating Occasions Not Reported, Outcome
173 | Chaouachi A, Chamari K, Roky R, Wong P, Mbazaa A, Bartagi Z, Amri M. Lipid profiles of judo athletes during Ramadan. Int J Sports Med. 2008. 29:282–8 https://www.ncbi.nlm.nih.gov/pubmed/17879887 | Daily Eating Occasions Not Reported
174 | Chaouachi A, Coutts AJ, Chamari K, Wong del P, Chaouachi M, Chtara M, Roky R, Amri M. Effect of Ramadan intermittent fasting on aerobic and anaerobic performance and perception of fatigue in male elite judo athletes. J Strength Cond Res. 2009. 23:2702–9 https://www.ncbi.nlm.nih.gov/pubmed/19910805 | Outcome
175 | Chapelot D, Marmonier C, Aubert R, Allegre C, Gausseres N, Fantino M, Louis-Sylvestre J. Consequence of omitting or adding a meal in man on body composition, food intake, and metabolism. Obesity (Silver Spring). 2006. 14:215–27 https://www.ncbi.nlm.nih.gov/pubmed/16571846 | Size of Study Groups
176 | Chapelot D, Chapelot D. The role of snacking in energy balance: a biobehavioral approach. Journal of nutrition. 2011;141(1):158–62. https://www.ncbi.nlm.nih.gov/pubmed/21123465. | Study Design, Publication Status
177 | Chapuis-de-Andrade S, de Araujo RM, Lara DR. Association of weight control behaviors with body mass index and weight-based self-evaluation. Braz J Psychiatry. 2017. 39:237–243 https://www.ncbi.nlm.nih.gov/pubmed/28355342 | Study Design
178 | Chaput JP, Despres JP, Bouchard C, Tremblay A. The association between short sleep duration and weight gain is dependent on disinhibited eating behavior in adults. Sleep. 2011. 34:1291–7 https://www.ncbi.nlm.nih.gov/pubmed/21966060 | Intervention/Exposure, Daily Eating Occasions Not Reported
179 | Chaput JP, Leblanc C, Perusse L, Despres JP, Bouchard C, Tremblay A. Risk factors for adult overweight and obesity in the Quebec Family Study: have we been barking up the wrong tree?. Obesity (Silver Spring). 2009. 17:1964–70 https://www.ncbi.nlm.nih.gov/pubmed/19360005 | Study Design
180 | Chen CY, Hsiao YC. Dual trajectories of breakfast eating and fruit and vegetable intake over a 5-year follow-up period among economically disadvantaged children: Gender differences. Appetite. 2018. 121:41–49 https://www.ncbi.nlm.nih.gov/pubmed/29079477 | Daily Eating Occasions Not Reported, Duplicate
181 | Chen HJ, Wang Y, Cheskin LJ. Relationship between frequency of eating and cardiovascular disease mortality in U.S. adults: the NHANES III follow-up study. Ann Epidemiol. 2016. 26:527–533 https://www.ncbi.nlm.nih.gov/pubmed/27397905 | Eating Frequency Data Collection
182 | Chennaoui M, Desgorces F, Drogou C, Boudjemaa B, Tomaszewski A, Depiesse F, Burnat P, Chalabi H, Gomez-Merino D. Effects of Ramadan fasting on physical performance and metabolic, hormonal, and inflammatory parameters in middle-distance runners. Appl Physiol Nutr Metab. 2009. 34:587–94 https://www.ncbi.nlm.nih.gov/pubmed/19767792 | Daily Eating Occasions Not Reported
183 | Cherif A, Meeusen R, Farooq A, Ryu J, Fenneni MA, Nikolovski Z, Elshafie S, Chamari K, Roelands B. Three Days of Intermittent Fasting: Repeated-Sprint Performance Decreased by Vertical-Stiffness Impairment. Int J Sports Physiol Perform. 2017. 12:287–294 https://www.ncbi.nlm.nih.gov/pubmed/27248138 | Daily Eating Occasions Not Reported
184 | Chihaoui M, Grira W, Bettaieb J, Yazidi M, Chaker F, Rejeb O, Oueslati I, Feki M, Kaabachi N, Slimane H. The risk for hypoglycemia during Ramadan fasting in patients with adrenal insufficiency. Nutrition. 2018. 45:99–103 https://www.ncbi.nlm.nih.gov/pubmed/29129244 | Daily Eating Occasions Not Reported, Health Status
185 | Cho AR, Moon JY, Kim S, An KY, Oh M, Jeon JY, Jung DH, Choi MH, Lee JW. Effects of alternate day fasting and exercise on cholesterol metabolism in overweight or obese adults: A pilot randomized controlled trial. Metabolism. 2019. 93:52–60 https://www.ncbi.nlm.nih.gov/pubmed/30615947 | Daily Eating Occasions Not Reported
186 | Chowdhury EA, Richardson JD, Holman GD, Tsintzas K, Thompson D, Betts JA. The causal role of breakfast in energy balance and health: a randomized controlled trial in obese adults. Am J Clin Nutr. 2016. 103:747–56 https://www.ncbi.nlm.nih.gov/pubmed/26864365 | Daily Eating Occasions Not Reported
187 | Chowdhury EA, Richardson JD, Tsintzas K, Thompson D, Betts JA. Carbohydrate-rich breakfast attenuates glycaemic, insulinaemic and ghrelin response to ad libitum lunch relative to morning fasting in lean adults. Br J Nutr. 2015. 114:98–107 https://www.ncbi.nlm.nih.gov/pubmed/26004166 | Daily Eating Occasions Not Reported
188 | Chowdhury EA, Richardson JD, Tsintzas K, Thompson D, Betts JA. Effect of extended morning fasting upon ad libitum lunch intake and associated metabolic and hormonal responses in obese adults. Int J Obes (Lond). 2016. 40:305–11 https://www.ncbi.nlm.nih.gov/pubmed/26278005 | Daily Eating Occasions Not Reported
189 | Chowdhury EA, Richardson JD, Tsintzas K, Thompson D, Betts JA. Postprandial Metabolism and Appetite Do Not Differ between Lean Adults that Eat Breakfast or Morning Fast for 6 Weeks. J Nutr. 2018. 148:13–21 https://www.ncbi.nlm.nih.gov/pubmed/29378040 | Daily Eating Occasions Not Reported, Size of Study Groups
190 | Christenson A, Johansson E, Reynisdottir S, Torgerson J, Hemmingsson E. Women’s Perceived Reasons for Their Excessive Postpartum Weight Retention: A Qualitative Interview Study. PLoS One. 2016. 11:e0167731 https://www.ncbi.nlm.nih.gov/pubmed/27936110 | Study Design
191 | Ciangherotti S, Kevicka K, Ciangherotti E, Rondinone R. Eating behaviour: research in Liguria on young, adult and elderly subjects. J Prev Med Hyg. 2006. 47:26–36 https://www.ncbi.nlm.nih.gov/pubmed/17061408 | Study Design, Outcome
192 | Ciccone J, Woodruff SJ, Fryer K, Campbell T, Cole M. Associations among evening snacking, screen time, weight status, and overall diet quality in young adolescents. Appl Physiol Nutr Metab. 2013. 38:789–94 https://www.ncbi.nlm.nih.gov/pubmed/23980738 | Study Design
193 | Clayton DJ, Biddle J, Maher T, Funnell MP, Sargeant JA, King JA, Hulston CJ, Stensel DJ, James LJ. 24-h severe energy restriction impairs postprandial glycaemic control in young, lean males. Br J Nutr. 2018. 120:1107–1116 https://www.ncbi.nlm.nih.gov/pubmed/30401004 | Comparator, Size of Study Groups
194 | Clayton DJ, Creese M, Skidmore N, Stensel DJ, James LJ. No effect of 24 h severe energy restriction on appetite regulation and ad libitum energy intake in overweight and obese males. Int J Obes (Lond). 2016. 40:1662–1670 https://www.ncbi.nlm.nih.gov/pubmed/27339607 | Daily Eating Occasions Not Reported
195 | Clayton DJ, Stensel DJ, James LJ. Effect of breakfast omission on subjective appetite, metabolism, acylated ghrelin and GLP-17-36 during rest and exercise. Nutrition. 2016. 32:179–85 https://www.ncbi.nlm.nih.gov/pubmed/26421384 | Eating Frequency Data Collection, Size of Study Groups
196 | Cleator J, Judd P, James M, Abbott J, Sutton CJ, Wilding JP. Characteristics and perspectives of night-eating behaviour in a severely obese population. Clin Obes. 2014. 4:30–8 https://www.ncbi.nlm.nih.gov/pubmed/25425130 | Study Design
197 | Clifford LM, Beebe DW, Simon SL, Kuhl ES, Filigno SS, Rausch JR, Stark LJ. The association between sleep duration and weight in treatment-seeking preschoolers with obesity. Sleep Med. 2012. 13:1102–5 https://www.ncbi.nlm.nih.gov/pubmed/22841032 | Intervention/Exposure, Daily Eating Occasions Not Reported
198 | Colles SL, Dixon JB, O’Brien PE. Night eating syndrome and nocturnal snacking: association with obesity, binge eating and psychological distress. Int J Obes (Lond). 2007. 31:1722–30 https://www.ncbi.nlm.nih.gov/pubmed/17579633 | Intervention/Exposure, Daily Eating Occasions Not Reported
199 | Conley M, Le Fevre L, Haywood C, Proietto J. Is two days of intermittent energy restriction per week a feasible weight loss approach in obese males? A randomised pilot study. Nutr Diet. 2018. 75:65–72 https://www.ncbi.nlm.nih.gov/pubmed/28791787 | Daily Eating Occasions Not Reported
200 | Conti K. Nutrition status of American Indian adults and impending needs in view of the strong heart dietary study. J Am Diet Assoc. 2008. 108:781–4 https://www.ncbi.nlm.nih.gov/pubmed/18442499 | Study Design
201 | Coppinger T, Jeanes YM, Hardwick J, Reeves S. Body mass, frequency of eating and breakfast consumption in 9-13-year-olds. J Hum Nutr Diet. 2012. 25:43–9 https://www.ncbi.nlm.nih.gov/pubmed/21649747 | Study Design
202 | Corbalan-Tutau MD, Madrid JA, Garaulet M. Timing and duration of sleep and meals in obese and normal weight women. Association with increase blood pressure. Appetite. 2012. 59:9–16 https://www.ncbi.nlm.nih.gov/pubmed/22450522 | Study Design
203 | Corder K, van Sluijs EM, Ridgway CL, Steele RM, Prynne CJ, Stephen AM, Bamber DJ, Dunn VJ, Goodyer IM, Ekelund U. Breakfast consumption and physical activity in adolescents: daily associations and hourly patterns. Am J Clin Nutr. 2014. 99:361–8 https://www.ncbi.nlm.nih.gov/pubmed/24284440 | Study Design
204 | Corder K, van Sluijs EM, Steele RM, Stephen AM, Dunn V, Bamber D, Goodyer I, Griffin SJ, Ekelund U. Breakfast consumption and physical activity in British adolescents. Br J Nutr. 2011. 105:316–21 https://www.ncbi.nlm.nih.gov/pubmed/20807464 | Study Design
205 | Corley B, Khouri C, Theaude L, Hawke P, Hall R, Weatherall M, Krebs J. Changes in resting energy expenditure with intermittent fasting versus continuous daily restriction-a randomised controlled trial. Internal medicine journal. 2019. 49:5 | Study Design, Publication Status
206 | Coronary artery disease. J Pract Nurs. 2008. 58:14–20 https://www.ncbi.nlm.nih.gov/pubmed/19260363 | Study Design
207 | Correa-Arruda WS, Vaez IDA, Aguilar-Nascimento JE, Dock-Nascimento DB. Effects of overnight fasting on handgrip strength in inpatients. Einstein (Sao Paulo). 2019. 17:eAO4418 https://www.ncbi.nlm.nih.gov/pubmed/30652738 | Daily Eating Occasions Not Reported
208 | Coutinho SR, Glsbakk S, Halset EH, Kulseng B, Truby H, Martins C. Effect of intermittent versus continuous energy restriction on compensatory mechanisms activated during weight reduction. Obesity facts. 2015. 8:107 | Publication Status
209 | Coutinho SR, Halset EH, Gasbakk S, Rehfeld JF, Kulseng B, Truby H, Martins C. Compensatory mechanisms activated with intermittent energy restriction: A randomized control trial. Clin Nutr. 2018. 37:815–823 https://www.ncbi.nlm.nih.gov/pubmed/28446382 | Daily Eating Occasions Not Reported, Size of Study Groups
210 | Cowley G. The ultimate diet plan. Don’t eat so much. Newsweek. 2001. 137:53 | Study Design, Publication Status
211 | Crimarco A, Turner-McGrievy GM, Wirth MD. The effects of meal-timing on self-rated hunger and dietary inflammatory potential among a sample of college students. J Am Coll Health. 2019. 67:328–337 https://www.ncbi.nlm.nih.gov/pubmed/29979952 | Intervention/Exposure
212 | Culnan E, Kloss JD, Grandner M. A prospective study of weight gain associated with chronotype among college freshmen. Chronobiol Int. 2013. 30:682–90 https://www.ncbi.nlm.nih.gov/pubmed/23688114 | Intervention/Exposure, Daily Eating Occasions Not Reported
213 | Daniels SR. Clues to concerns about eating and weight in adolescents. Journal of Pediatrics. 2010. 157:A2 | Study Design
214 | Dannecker EA, Liu Y, Rector RS, Thomas TR, Sayers SP, Leeuwenburgh C, Ray BK. The effect of fasting on indicators of muscle damage. Exp Gerontol. 2013. 48:1101–6 https://www.ncbi.nlm.nih.gov/pubmed/23266375 | Daily Eating Occasions Not Reported, Comparator
215 | D’Arrigo T. Snack attack. Night-eating syndrome is no joke. Diabetes Forecast. 2007. 60:20 https://www.ncbi.nlm.nih.gov/pubmed/17941142 | Study Design, Publication Status
216 | Das SK, Saltzman E, Gilhooly CH, DeLany JP, Golden JK, Pittas AG, Dallal GE, Bhapkar MV, Fuss PJ, Dutta C, McCrory MA, Roberts SB. Low or moderate dietary energy restriction for long-term weight loss: what works best?. Obesity (Silver Spring). 2009. 17:2019–24 https://www.ncbi.nlm.nih.gov/pubmed/19390525 | Intervention/Exposure, Daily Eating Occasions Not Reported
217 | Dashti HS, Merino J, Lane JM, Song Y, Smith CE, Tanaka T, McKeown NM, Tucker C, Sun D, Bartz TM, Li-Gao R, Nisa H, Reutrakul S, Lemaitre RN, Alshehri TM, de Mutsert R, Bazzano L, Qi L, Knutson KL, Psaty BM, Mook-Kanamori DO, Perica VB, Neuhouser ML, Fajl Scheer, Rutter MK, Garaulet M, Saxena R. Genome-wide association study of breakfast skipping links clock regulation with food timing. Am J Clin Nutr. 2019. 110:473–484 https://www.ncbi.nlm.nih.gov/pubmed/31190057 | Intervention/Exposure, Daily Eating Occasions Not Reported, Outcome
218 | Dattilo M, Crispim CA, Zimberg IZ, Tufik S, De Mello MT. Meal distribution across the day and its relationship with body composition. Biological Rhythm Research. 2011. 42:119–129 | Study Design
219 | Davis AM, Canter KS, Stough CO, Gillette MD, Patton S. Measurement of mealtime behaviors in rural overweight children: an exploratory factor analysis of the Behavioral Pediatrics Feeding Assessment Scale. J Pediatr Psychol. 2014. 39:332–9 https://www.ncbi.nlm.nih.gov/pubmed/24326908 | Study Design, Intervention/Exposure, Daily Eating Occasions Not Reported
220 | de Castro JM. In search of the structure of a function: the eating behavior of free-living humans. Nutrition. 2007. 23:374–377 | Study Design
221 | De Sousa A. Maternal, child and family factors in childhood obesity. International Journal of Diabetes and Metabolism. 2009. 17:111–112 | Study Design
222 | Della Libera B, Ribeiro Baiao M, de Souza Santos MM, Padilha P, Dutra Alves P, Saunders C. Adherence of pregnant women to dietary counseling and adequacy of total gestational weight gain. Nutr Hosp. 2011. 26:79–85 https://www.ncbi.nlm.nih.gov/pubmed/21519732 | Study Design
223 | Den inneren Schweinehund in den Griff kriegen. Kinderkrankenschwester. 2017;36(2):58. https://www.ncbi.nlm.nih.gov/pubmed/30379452. | Intervention/Exposure, Publication Status, Language
224 | Deniz CD, Ozler S, Sayin FK, Eryilmaz MA. Associations between night eating syndrome and metabolic parameters in pregnant women. Turk J Obstet Gynecol. 2019. 16:107–111 https://www.ncbi.nlm.nih.gov/pubmed/31360584 | Intervention/Exposure
225 | Dennis EA, Dengo AL, Comber DL, Flack KD, Savla J, Davy KP, Davy BM. Water consumption increases weight loss during a hypocaloric diet intervention in middle-aged and older adults. Obesity (Silver Spring). 2010. 18:300–7 https://www.ncbi.nlm.nih.gov/pubmed/19661958 | Intervention/Exposure
226 | Develioglu ON, Kucur M, Ipek HD, Celebi S, Can G, Kulekci M. Effects of Ramadan fasting on serum immunoglobulin G and M, and salivary immunoglobulin A concentrations. J Int Med Res. 2013. 41:463–72 https://www.ncbi.nlm.nih.gov/pubmed/23569012 | Intervention/Exposure, Daily Eating Occasions Not Reported
227 | Dewanti L, Watanabe C, Sulistiawati, Ohtsuka R. Unexpected changes in blood pressure and hematological parameters among fasting and nonfasting workers during Ramadan in Indonesia. Eur J Clin Nutr. 2006. 60:877–81 https://www.ncbi.nlm.nih.gov/pubmed/16489329 | Country
228 | Dhurandhar EJ, Dawson J, Alcorn A, Larsen LH, Thomas EA, Cardel M, Bourland AC, Astrup A, St-Onge MP, Hill JO, Apovian CM, Shikany JM, Allison DB. The effectiveness of breakfast recommendations on weight loss: a randomized controlled trial. Am J Clin Nutr. 2014. 100:507–13 https://www.ncbi.nlm.nih.gov/pubmed/24898236 | Daily Eating Occasions Not Reported
229 | Dikensoy E, Balat O, Cebesoy B, Ozkur A, Cicek H, Can G. Effect of fasting during Ramadan on fetal development and maternal health. J Obstet Gynaecol Res. 2008. 34:494–8 https://www.ncbi.nlm.nih.gov/pubmed/18937702 | Intervention/Exposure, Daily Eating Occasions Not Reported
230 | Dikensoy E, Balat O, Cebesoy B, Ozkur A, Cicek H, Can G. The effect of Ramadan fasting on maternal serum lipids, cortisol levels and fetal development. Arch Gynecol Obstet. 2009. 279:119–23 https://www.ncbi.nlm.nih.gov/pubmed/18488237 | Intervention/Exposure, Daily Eating Occasions Not Reported
231 | Dirks ML, Smeets JSJ, Holwerda AM, Kouw IWK, Marzuca-Nassr GN, Gijsen AP, Holloway GP, Verdijk LB, van Loon LJC. Dietary feeding pattern does not modulate the loss of muscle mass or the decline in metabolic health during short-term bed rest. Am J Physiol Endocrinol Metab. 2019. 316:E536–e545 https://www.ncbi.nlm.nih.gov/pubmed/30645176 | Intervention/Exposure, Comparator
232 | Dixit VD, Yang H, Sayeed KS, Stote KS, Rumpler WV, Baer DJ, Longo DL, Mattson MP, Taub DD. Controlled meal frequency without caloric restriction alters peripheral blood mononuclear cell cytokine production. J Inflamm (Lond). 2011. 8:6 https://www.ncbi.nlm.nih.gov/pubmed/21385360 | Outcome
233 | Dixon CB, Masteller B, Andreacci JL. The effect of a meal on measures of impedance and percent body fat estimated using contact-electrode bioelectrical impedance technology. Eur J Clin Nutr. 2013. 67:950–5 https://www.ncbi.nlm.nih.gov/pubmed/23820339 | Intervention/Exposure, Publication Status, Language
234 | Dong F, Howard AG, Herring AH, Thompson AL, Adair LS, Popkin BM, Aiello AE, Zhang B, Gordon-Larsen P. Longitudinal associations of away-from-home eating, snacking, screen time, and physical activity behaviors with cardiometabolic risk factors among Chinese children and their parents. Am J Clin Nutr. 2017. 106:168–178 https://www.ncbi.nlm.nih.gov/pubmed/28539376 | Intervention/Exposure, Daily Eating Occasions Not Reported
235 | Donnelly LS, Shaw RL, Pegington M, Armitage CJ, Evans DG, Howell A, Harvie MN. ‘For me it’s about not feeling like Im on a diet’: a thematic analysis of women’s experiences of an intermittent energy restricted diet to reduce breast cancer risk. J Hum Nutr Diet. 2018. 31:773–780 https://www.ncbi.nlm.nih.gov/pubmed/29926996 | Study Design, Size of Study Groups
236 | Dorflinger LM, Ruser CB, Masheb RM. Night eating among veterans with obesity. Appetite. 2017. 117:330–334 https://www.ncbi.nlm.nih.gov/pubmed/28711610 | Study Design, Intervention/Exposure
237 | Dosamantes-Carrasco LD, Mendez-Hernandez P, Flores YN, Siani C, Denova-Gutierrez E, Gallegos-Carrillo K, Ramirez P, Rivera-Paredez B, Salazar-Martinez E, Salmeron J. Influence of mealtime habits on the risk of weight gain and obesity in Mexican adults. Public Health Nutr. 2017. 20:220–232 https://www.ncbi.nlm.nih.gov/pubmed/27667585 | Intervention/Exposure
238 | Doucet E, Imbeault P, St-Pierre S, Almeras N, Mauriege P, Richard D, Tremblay A. Appetite after weight loss by energy restriction and a low-fat diet-exercise follow-up. Int J Obes Relat Metab Disord. 2000. 24:906–14 https://www.ncbi.nlm.nih.gov/pubmed/10918539 | Intervention/Exposure
239 | Drapeau V, Jacob R, Panahi S, Tremblay A. Effect of Energy Restriction on Eating Behavior Traits and Psychobehavioral Factors in the Low Satiety Phenotype. Nutrients. 2019;11(2). https://www.ncbi.nlm.nih.gov/pubmed/30678317. | Intervention/Exposure, Daily Eating Occasions Not Reported
240 | Drapeau V, Provencher V, Lemieux S, Despres JP, Bouchard C, Tremblay A. Do 6-y changes in eating behaviors predict changes in body weight? Results from the Quebec Family Study. Int J Obes Relat Metab Disord. 2003. 27:808–14 https://www.ncbi.nlm.nih.gov/pubmed/12821966 | Intervention/Exposure
241 | Dubois L, Girard M, Potvin Kent M. Breakfast eating and overweight in a pre-school population: is there a link?. Public Health Nutr. 2006. 9:436–42 https://www.ncbi.nlm.nih.gov/pubmed/16870015 | Daily Eating Occasions Not Reported
242 | Ducrot P, Mejean C, Bellisle F, Alles B, Hercberg S, Peneau S. Adherence to the French Eating Model is inversely associated with overweight and obesity: results from a large sample of French adults. Br J Nutr. 2018. 120:231–239 https://www.ncbi.nlm.nih.gov/pubmed/29781419 | Study Design
243 | Duffin C. Tackling childhood obesity across London. Paediatr Nurs. 2009. 21:8–9 https://www.ncbi.nlm.nih.gov/pubmed/19623796 | Study Design, Intervention/Exposure
244 | Duval K, Strychar I, Cyr MJ, Prud’homme D, Rabasa-Lhoret R, Doucet E. Physical activity is a confounding factor of the relation between eating frequency and body composition. Am J Clin Nutr. 2008. 88:1200–5 https://www.ncbi.nlm.nih.gov/pubmed/18996853 | Study Design
245 | Eat your breakfast. When it comes to good nutrition, mom really does know best. Diabetes Forecast. 2006. 59:43–5 https://www.ncbi.nlm.nih.gov/pubmed/16779888 | Study Design
246 | Eating less and often. Does it help weight control?. Mayo Clin Womens Healthsource. 2006. 10:9 https://www.ncbi.nlm.nih.gov/pubmed/16585927 | Study Design
247 | Edinburgh RM, Hengist A, Smith HA, Travers RL, Betts JA, Thompson D, Walhin JP, Wallis GA, Hamilton DL, Stevenson EJ, Tipton KD, Gonzalez JT. Skipping Breakfast Before Exercise Creates a More Negative 24-hour Energy Balance: A Randomized Controlled Trial in Healthy Physically Active Young Men. J Nutr. 2019. 149:1326–1334 https://www.ncbi.nlm.nih.gov/pubmed/31321428 | Intervention/Exposure
248 | Effect of circadian restricted meal on blood pressure in young hypertensive individuals. Journal of hypertension. 2018. 36:e312 | Study Design, Publication Status
249 | Effective dietary interventions for managing overweight and obesity in children. Nurs N Z. 2007. 13:30–1 https://www.ncbi.nlm.nih.gov/pubmed/17685044 | Study Design
250 | Elands RJJ, Offermans NSM, Ccjm Simons, Schouten LJ, Verhage BA, van den Brandt PA, Weijenberg MP. Associations of adult-attained height and early life energy restriction with postmenopausal breast cancer risk according to estrogen and progesterone receptor status. Int J Cancer. 2019. 144:1844–1857 https://www.ncbi.nlm.nih.gov/pubmed/30252931 | Outcome
251 | Elderkin AL, Bourbon A, Curtis LG, Dillard WC, Buskey RH, Nelson RL, Ulshafer C. Successes and challenges in treating obesity. Jaapa. 2002. 15:11–2, 15–6, 19 passim https://www.ncbi.nlm.nih.gov/pubmed/12474429 | Intervention/Exposure
252 | Elgar FJ, Xie A, Pfortner TK, White J, Pickett KE. Relative deprivation and risk factors for obesity in Canadian adolescents. Soc Sci Med. 2016. 152:111–8 https://www.ncbi.nlm.nih.gov/pubmed/26851410 | Study Design
253 | Elmehdawi R, Ehmida M, Elmagrehi H. Incidence of diabetic ketoacidosis during ramadan fasting in Benghazi-Libya. Oman Medical Journal. 2009;24(2):99–102. https://www.ncbi.nlm.nih.gov/pubmed/22334853. | Health Status
254 | El-Mitwalli A, Zaher AA, El Menshawi E. Circadian rhythm of stroke onset during the month of Ramadan. Acta Neurol Scand. 2010. 122:97–101 https://www.ncbi.nlm.nih.gov/pubmed/19839942 | Intervention/Exposure, Daily Eating Occasions Not Reported
255 | Enriquez E, Duncan GE, Schur EA. Age at dieting onset, body mass index, and dieting practices. A twin study. Appetite. 2013. 71:301–6 https://www.ncbi.nlm.nih.gov/pubmed/24025547 | Daily Eating Occasions Not Reported
256 | Erdem Y, Ozkan G, Ulusoy S, Arici M, Derici U, Sengul S, Sindel S, Erturk S. The effect of intermittent fasting on blood pressure variability in patients with newly diagnosed hypertension or prehypertension. J Am Soc Hypertens. 2018. 12:42–49 https://www.ncbi.nlm.nih.gov/pubmed/29275920 | Intervention/Exposure, Daily Eating Occasions Not Reported
257 | Erjavec M, Viktor S, Horne P, Lowe F. Implementing a healthy eating programme: changing children’s eating habits for life. Community Pract. 2012. 85:39–40, 42 https://www.ncbi.nlm.nih.gov/pubmed/22586868 | Study Design, Publication Status
258 | Erol A, Baylan G, Yazici F. Do Ramadan fasting restrictions alter eating behaviours?. Eur Eat Disord Rev. 2008. 16:297–301 https://www.ncbi.nlm.nih.gov/pubmed/18444254 | Intervention/Exposure, Daily Eating Occasions Not Reported, Outcome
259 | Eshghinia S, Mohammadzadeh F. The effects of modified alternate-day fasting diet on weight loss and CAD risk factors in overweight and obese women. J Diabetes Metab Disord. 2013. 12:4 https://www.ncbi.nlm.nih.gov/pubmed/23497604 | Intervention/Exposure, Daily Eating Occasions Not Reported
260 | Eslamian L, Ramezani Z. Breakfast as a screening test for gestational diabetes. International Journal of Gynecology and Obstetrics. 2007;96(1):34–5. https://www.ncbi.nlm.nih.gov/pubmed/17188692. | Intervention/Exposure, Daily Eating Occasions Not Reported, Publication Status
261 | Faerch K, Quist JS, Hulman A, Witte DR, Tabak AG, Brunner EJ, Kivimaki M, Jorgensen ME, Panda S, Vistisen D. Prospective association between late evening food consumption and risk of prediabetes and diabetes: the Whitehall II cohort study. Diabet Med. 2019. https://www.ncbi.nlm.nih.gov/pubmed/30897241 | Intervention/Exposure, Daily Eating Occasions Not Reported
262 | Fahey MC, Wayne Talcott G, Cox Bauer CM, Bursac Z, Gladney L, Hare ME, et al. Moms fit 2 fight: rationale, design, and analysis plan of a behavioral weight management intervention for pregnant and postpartum women in the U.S. military. Contemporary clinical trials. 2018;74:46–54. https://www.ncbi.nlm.nih.gov/pubmed/30291998. | Study Design
263 | Fang CT, Chen VC, Ma HT, Chao HH, Ho MC, Gossop M. Attentional Bias, “Cool” and “Hot” Executive Functions in Obese Patients: Roles of Body Mass Index, Binge Eating, and Eating Style. J Clin Psychopharmacol. 2019. 39:145–152 https://www.ncbi.nlm.nih.gov/pubmed/30742591 | Intervention/Exposure, Outcome
264 | Faria-Schutzer DB, Surita FG, Rodrigues L, Turato ER. Eating Behaviors in Postpartum: A Qualitative Study of Women with Obesity. Nutrients. 2018;10(7). https://www.ncbi.nlm.nih.gov/pubmed/29996489. | Study Design
265 | Faris MA, Hussein RN, Al-Kurd RA, Al-Fararjeh MA, Bustanji YK, Mohammad MK. Impact of ramadan intermittent fasting on oxidative stress measured by urinary 15-f(2t)-isoprostane. J Nutr Metab. 2012. 2012:802924 https://www.ncbi.nlm.nih.gov/pubmed/23150812 | Daily Eating Occasions Not Reported
266 | Faris MAE, Madkour MI, Obaideen AK, Dalah EZ, Hasan HA, Radwan H, Jahrami HA, Hamdy O, Mohammad MG. Effect of Ramadan diurnal fasting on visceral adiposity and serum adipokines in overweight and obese individuals. Diabetes Res Clin Pract. 2019. 153:166–175 https://www.ncbi.nlm.nih.gov/pubmed/31150725 | Daily Eating Occasions Not Reported
267 | Farooq A, Herrera CP, Almudahka F, Mansour R. A Prospective Study of the Physiological and Neurobehavioral Effects of Ramadan Fasting in Preteen and Teenage Boys. J Acad Nutr Diet. 2015. 115:889–97 https://www.ncbi.nlm.nih.gov/pubmed/25840939 | Intervention/Exposure, Daily Eating Occasions Not Reported
268 | Farshchi HR,Taylor MA, Macdonald IA. Beneficial metabolic effects of regular meal frequency on dietary thermogenesis, insulin sensitivity, and fasting lipid profiles in healthy obese women. Am J Clin Nutr. 2005. 81:16–24 https://www.ncbi.nlm.nih.gov/pubmed/15640455 | Size of Study Groups
269 | Farshchi HR, Taylor MA, Macdonald IA. Deleterious effects of omitting breakfast on insulin sensitivity and fasting lipid profiles in healthy lean women. Am J Clin Nutr. 2005. 81:388–96 https://www.ncbi.nlm.nih.gov/pubmed/15699226 | Comparator
270 | Farshchi HR, Taylor MA, Macdonald IA. Regular meal frequency creates more appropriate insulin sensitivity and lipid profiles compared with irregular meal frequency in healthy lean women. Eur J Clin Nutr. 2004. 58:1071–7 https://www.ncbi.nlm.nih.gov/pubmed/15220950 | Size of Study Groups
271 | Fawzi MH, Fawzi MM, Said NS, Fawzi MM, Fouad AA, Abdel-Moety H. Effect of Ramadan fasting on anthropometric, metabolic, inflammatory and psychopathology status of Egyptian male patients with schizophrenia. Psychiatry Res. 2015. 225:501–8 https://www.ncbi.nlm.nih.gov/pubmed/25529262 | Daily Eating Occasions Not Reported, Health Status
272 | Fayet-Moore F, McConnell A, Cassettari T, Petocz P. Breakfast Choice Is Associated with Nutrient, Food Group and Discretionary Intakes in Australian Adults at Both Breakfast and the Rest of the Day. Nutrients. 2019;11(1). https://www.ncbi.nlm.nih.gov/pubmed/30650604 | Study Design
273 | Feeley AB, Musenge E, Pettifor JM, Norris SA. Investigation into longitudinal dietary behaviours and household socio-economic indicators and their association with BMI Z-score and fat mass in South African adolescents: the Birth to Twenty (Bt20) cohort. Public Health Nutr. 2013. 16:693–703 https://www.ncbi.nlm.nih.gov/pubmed/22801035 | Daily Eating Occasions Not Reported
274 | Fehler KL, Kennedy LE, McCargar LJ, Bell RC, Ryan EA. Postpartum dietary changes in women with previous gestational diabetes mellitus. Canadian Journal of Diabetes. 2007. 31:54–61 | Intervention/Exposure, Daily Eating Occasions Not Reported
275 | Feig EH, Piers AD, Kral TVE, Lowe MR. Eating in the absence of hunger is related to loss-of-control eating, hedonic hunger, and short-term weight gain in normal-weight women. Appetite. 2018. 123:317–324 https://www.ncbi.nlm.nih.gov/pubmed/29331366 | Intervention/Exposure, Daily Eating Occasions Not Reported
276 | Feizollahzadeh S, Rasuli J, Kheirouri S, Alizadeh M. Augmented plasma adiponectin after prolonged fasting during ramadan in men. Health Promot Perspect. 2014. 4:77–81 https://www.ncbi.nlm.nih.gov/pubmed/25097840 | Intervention/Exposure, Daily Eating Occasions Not Reported
277 | Feller S, Muller A, Mayr A, Engeli S, Hilbert A, de Zwaan M. What distinguishes weight loss maintainers of the German Weight Control Registry from the general population?. Obesity (Silver Spring). 2015. 23:1112–8 https://www.ncbi.nlm.nih.gov/pubmed/25864871 | Study Design
278 | Fenneni MA, Latiri I, Aloui A, Rouatbi S, Saafi MA, Bougmiza I, Chamari K, Ben Saad H. Effects of Ramadan on physical capacities of North African boys fasting for the first time. Libyan J Med. 2014. 9:25391 https://www.ncbi.nlm.nih.gov/pubmed/25261691 | Intervention/Exposure, Daily Eating Occasions Not Reported
279 | Fernandez Morales I, Aguilar Vilas MV, Mateos Vega CJ, Martinez Para MC. Breakfast quality and its relationship to the prevalence of overweight and obesity in adolescents in Guadalajara (Spain). Nutr Hosp. 2011. 26:952–8 https://www.ncbi.nlm.nih.gov/pubmed/22072337 | Study Design
280 | Ferraris C, Marcolin G, Veneto A, Tagliabue A, Paoli A. Time restricted feeding in high-level athletes: a pilot study. Nutrition, metabolism and cardiovascular diseases. 2019. 29:877–878 | Study Design, Publication Status
281 | Ferreira SR, Gimeno SG, Hirai AT, Harima H, Matsumura L, Pittito Bde A. Effects of an intervention in eating habits and physical activity in Japanese-Brazilian women with a high prevalence of metabolic syndrome in Bauru, Sao Paulo State, Brazil. Cad Saude Publica. 2008. 24 Suppl 2:S294–302 https://www.ncbi.nlm.nih.gov/pubmed/18670709 | Study Design
282 | Ferrie JE, Kivimaki M, Akbaraly TN, Tabak A, Abell J, Davey Smith G, Virtanen M, Kumari M, Shipley MJ. Change in Sleep Duration and Type 2 Diabetes: The Whitehall II Study. Diabetes Care. 2015. 38:1467–72 https://www.ncbi.nlm.nih.gov/pubmed/26068863 | Intervention/Exposure
283 | Field AE, Austin SB, Gillman MW, Rosner B, Rockett HR, Colditz GA. Snack food intake does not predict weight change among children and adolescents. Int J Obes Relat Metab Disord. 2004. 28:1210–6 https://www.ncbi.nlm.nih.gov/pubmed/15314623 | Intervention/Exposure, Daily Eating Occasions Not Reported
284 | Field AE, Austin SB, Taylor CB, Malspeis S, Rosner B, Rockett HR, Gillman MW, Colditz GA. Relation between dieting and weight change among preadolescents and adolescents. Pediatrics. 2003. 112:900–6 https://www.ncbi.nlm.nih.gov/pubmed/14523184 | Intervention/Exposure, Daily Eating Occasions Not Reported
285 | Fineberg HV. An economic analysis of eating and physical activity behaviors: exploring effective strategies to combat obesity. Am J Prev Med. 2004. 27:172–4 https://www.ncbi.nlm.nih.gov/pubmed/15450628 | Study Design
286 | Finlayson G, Cecil J, Higgs S, Hill A, Hetherington M. Susceptibility to weight gain. Eating behaviour traits and physical activity as predictors of weight gain during the first year of university. Appetite. 2012. 58:1091–8 https://www.ncbi.nlm.nih.gov/pubmed/22407132 | Intervention/Exposure
287 | Firouzbakht M, Kiapour A, Jamali B, Kazeminavaei F, Taghlilin F, Ali Morad Heidari G. Fasting in pregnancy: A survey of beliefs and manners of Muslim women about Ramadan fasting. Annals of Tropical Medicine & Public Health. 2013;6(5):536–40. | Study Design, Daily Eating Occasions Not Reported
288 | Fletcher BJ, Oka R. Introduction: successful lifestyle changes for cardiovascular risk reduction. J Cardiovasc Nurs. 2010. 25:221–2 https://www.ncbi.nlm.nih.gov/pubmed/20386244 | Study Design
289 | Fogteloo AJ, Pijl H, Roelfsema F, Frolich M, Meinders AE. Impact of meal timing and frequency on the twenty-four-hour leptin rhythm. Horm Res. 2004. 62:71–8 https://www.ncbi.nlm.nih.gov/pubmed/15218336 | Size of Study Groups
290 | Ford AL, Bergh C, Sodersten P, Sabin MA, Hollinghurst S, Hunt LP, Shield JP. Treatment of childhood obesity by retraining eating behaviour: randomised controlled trial. Bmj. 2009. 340:b5388 https://www.ncbi.nlm.nih.gov/pubmed/20051465 | Intervention/Exposure, Daily Eating Occasions Not Reported
291 | Forkert ECO, Moraes ACF, Carvalho HB, Manios Y, Widhalm K, Gonzalez-Gross M, Gutierrez A, Kafatos A, Censi L, De Henauw S, Moreno LA. Skipping breakfast is associated with adiposity markers especially when sleep time is adequate in adolescents. Sci Rep. 2019. 9:6380 https://www.ncbi.nlm.nih.gov/pubmed/31011180 | Study Design
292 | Fournier T, Tibere L, Laporte C, Mognard E, Ismail MN, Sharif SP, Poulain JP. Eating patterns and prevalence of obesity. Lessons learned from the Malaysian Food Barometer. Appetite. 2016. 107:362–371 https://www.ncbi.nlm.nih.gov/pubmed/27521166 | Study Design
293 | Francis LA, Lee Y, Birch LL. Parental weight status and girls television viewing, snacking, and body mass indexes. Obes Res. 2003. 11:143–51 https://www.ncbi.nlm.nih.gov/pubmed/12529497 | Daily Eating Occasions Not Reported
294 | Franko DL, Striegel-Moore RH, Thompson D, Affenito SG, Schreiber GB, Daniels SR, Crawford PB. The relationship between meal frequency and body mass index in black and white adolescent girls: more is less. Int J Obes (Lond). 2008. 32:23–9 https://www.ncbi.nlm.nih.gov/pubmed/17563764 | Study Design
295 | Freitas Junior IF, Christofaro DG, Codogno JS, Monteiro PA, Silveira LS, Fernandes RA. The association between skipping breakfast and biochemical variables in sedentary obese children and adolescents. J Pediatr. 2012. 161:871–4 https://www.ncbi.nlm.nih.gov/pubmed/22682613 | Study Design
296 | Fuglestad PT, Jeffery RW, Sherwood NE. Lifestyle patterns associated with diet, physical activity, body mass index and amount of recent weight loss in a sample of successful weight losers. Int J Behav Nutr Phys Act. 2012. 9:79 https://www.ncbi.nlm.nih.gov/pubmed/22734914 | Study Design
297 | Fujiwara T. Skipping breakfast is associated with dysmenorrhea in young women in Japan. Int J Food Sci Nutr. 2003. 54:505–9 https://www.ncbi.nlm.nih.gov/pubmed/14522696 | Study Design, Intervention/Exposure, Daily Eating Occasions Not Reported, Outcome
298 | Fullick S, Morris C, Jones H, Atkinson G. Prior exercise lowers blood pressure during simulated night-work with different meal schedules. American journal of hypertension. 2009;22(8):835–41. https://www.ncbi.nlm.nih.gov/pubmed/19556971. | Intervention/Exposure
299 | Gabašová E, Béder I, Babinská K, Béderová A, Turecký L, Uhlíková E. Nutritional behaviour among college students in Slovakia as one of the cardiovascular disease risk factors. Homeostasis in Health and Disease. 2004. 43:106–108 | Intervention/Exposure
300 | Gabel K, Hoddy KK, Burgess HJ, Varady KA. Effect of 8-h time-restricted feeding on sleep quality and duration in adults with obesity. Appl Physiol Nutr Metab. 2019. 44:903–906 https://www.ncbi.nlm.nih.gov/pubmed/30802152 | Daily Eating Occasions Not Reported, Eating Frequency Data Collection
301 | Gabel K, Hoddy KK, Haggerty N, Song J, Kroeger CM, Trepanowski JF, Panda S, Varady KA. Effects of 8-hour time restricted feeding on body weight and metabolic disease risk factors in obese adults: A pilot study. Nutr Healthy Aging. 2018. 4:345–353 https://www.ncbi.nlm.nih.gov/pubmed/29951594 | Daily Eating Occasions Not Reported, Size of Study Groups
302 | Gabel K, Hoddy KK, Varady KA. Safety of 8-h time restricted feeding in adults with obesity. Appl Physiol Nutr Metab. 2019. 44:107–109 https://www.ncbi.nlm.nih.gov/pubmed/30216730 | Daily Eating Occasions Not Reported
303 | Gabel K, Kroeger CM, Trepanowski JF, Hoddy KK, Cienfuegos S, Kalam F, Varady KA. Differential Effects of Alternate-Day Fasting Versus Daily Calorie Restriction on Insulin Resistance. Obesity (Silver Spring). 2019. 27:1443–1450 https://www.ncbi.nlm.nih.gov/pubmed/31328895 | Intervention/Exposure, Daily Eating Occasions Not Reported
304 | Gail Gates, Perera T. Association between Breakfast Consumption and Nutritional Status in 9 to 13 Year Old Children. Journal of Nutrition Education & Behavior. 2013. 45:S31–S31 | Study Design, Publication Status
305 | Gallant A, Drapeau V, Allison KC, Tremblay A, Lambert M, O’Loughlin J, Lundgren JD. Night eating behavior and metabolic heath in mothers and fathers enrolled in the QUALITY cohort study. Eat Behav. 2014. 15:186–91 https://www.ncbi.nlm.nih.gov/pubmed/24854802 | Study Design
306 | Gallant A, Lundgren J, O’Loughlin J, Allison K, Tremblay A, Henderson M, Drapeau V. Night-eating symptoms and 2-year weight change in parents enrolled in the QUALITY cohort. Int J Obes (Lond). 2015. 39:1161–5 https://www.ncbi.nlm.nih.gov/pubmed/25797608 | Intervention/Exposure, Daily Eating Occasions Not Reported
307 | Galson SK. Childhood overweight and obesity prevention. Public Health Rep. 2008. 123:258–9 https://www.ncbi.nlm.nih.gov/pubmed/19006963 | Study Design
308 | Garaulet M, Gomez-Abellan P, Alburquerque-Bejar JJ, Lee YC, Ordovas JM, Scheer FA. Timing of food intake predicts weight loss effectiveness. Int J Obes (Lond). 2013. 37:604–11 https://www.ncbi.nlm.nih.gov/pubmed/23357955 | Intervention/Exposure
309 | Garaulet M, Ortega FB, Ruiz JR, Rey-Lopez JP, Beghin L, Manios Y, Cuenca-Garcia M, Plada M, Diethelm K, Kafatos A, Molnar D, Al-Tahan J, Moreno LA. Short sleep duration is associated with increased obesity markers in European adolescents: effect of physical activity and dietary habits. The HELENA study. Int J Obes (Lond). 2011. 35:1308–17 https://www.ncbi.nlm.nih.gov/pubmed/21792170 | Study Design
310 | Garaulet M, Vera B, Bonnet-Rubio G, Gomez-Abellan P, Lee YC, Ordovas JM. Lunch eating predicts weight-loss effectiveness in carriers of the common allele at PERILIPIN1: the ONTIME (Obesity, Nutrigenetics, Timing, Mediterranean) study. Am J Clin Nutr. 2016. 104:1160–1166 https://www.ncbi.nlm.nih.gov/pubmed/27629052 | Intervention/Exposure, Daily Eating Occasions Not Reported
311 | Geliebter A, Astbury NM, Aviram-Friedman R, Yahav E, Hashim S. Skipping breakfast leads to weight loss but also elevated cholesterol compared with consuming daily breakfasts of oat porridge or frosted cornflakes in overweight individuals: a randomised controlled trial. J Nutr Sci. 2014. 3:e56 https://www.ncbi.nlm.nih.gov/pubmed/26101624 | Daily Eating Occasions Not Reported
312 | Geliebter A, Gluck ME, Tanowitz M, Aronoff NJ, Zammit GK. Work-shift period and weight change. Nutrition. 2000. 16:27–9 https://www.ncbi.nlm.nih.gov/pubmed/10674231 | Intervention/Exposure, Daily Eating Occasions Not Reported
313 | Gerage AM, Benedetti TRB, Ritti-Dias RM, Dos Santos ACO, de Souza BCC, Almeida FA. Effectiveness of a Behavior Change Program on Physical Activity and Eating Habits in Patients With Hypertension: A Randomized Controlled Trial. J Phys Act Health. 2017. 14:943–952 https://www.ncbi.nlm.nih.gov/pubmed/28682707 | Intervention/Exposure
314 | Gibson P. Childhood obesity: an approach to weight management. J Fam Health Care. 2002. 12:88–9 https://www.ncbi.nlm.nih.gov/pubmed/12416013 | Study Design
315 | Gilardini L, Croci M, Pasqualinotto L, Caffetto K, Invitti C. Dietary Habits and Cardiometabolic Health in Obese Children. Obes Facts. 2015. 8:101–9 https://www.ncbi.nlm.nih.gov/pubmed/26087840 | Study Design
316 | Gill S, Panda S. A Smartphone App Reveals Erratic Diurnal Eating Patterns in Humans that Can Be Modulated for Health Benefits. Cell Metab. 2015. 22:789–98 https://www.ncbi.nlm.nih.gov/pubmed/26411343 | Study Design, Intervention/Exposure, Outcome
317 | Gingras V, Rifas-Shiman SL, Taveras EM, Oken E, Hivert MF. Dietary behaviors throughout childhood are associated with adiposity and estimated insulin resistance in early adolescence: a longitudinal study. Int J Behav Nutr Phys Act. 2018. 15:129 https://www.ncbi.nlm.nih.gov/pubmed/30558613 | Daily Eating Occasions Not Reported
318 | Giorgio C, Monica M, Margherita T, Elisabetta F, Filippo R. Study of the eating habits of the students attending the first 2 years at high school in Italy. Mediterranean Journal of Nutrition and Metabolism. 2013. 6:143–150 | Study Design, Daily Eating Occasions Not Reported
319 | Giudice R, Izzo R, Manzi MV, Pagnano G, Santoro M, Rao MA, Di Renzo G, De Luca N, Trimarco V. Lifestylerelated risk factors, smoking status and cardiovascular disease. High Blood Press Cardiovasc Prev. 2012. 19:85–92 https://www.ncbi.nlm.nih.gov/pubmed/22867094 | Study Design
320 | Gluck ME, Geliebter A, Satov T. Night eating syndrome is associated with depression, low self-esteem, reduced daytime hunger, and less weight loss in obese outpatients. Obes Res. 2001. 9:264–7 https://www.ncbi.nlm.nih.gov/pubmed/11331430 | Intervention/Exposure, Daily Eating Occasions Not Reported
321 | Gluck ME, Venti CA, Salbe AD, Krakoff J. Nighttime eating: Commonly observed and related to weight gain in an inpatient food intake study. American journal of clinical nutrition. 2008;88(4):900–5. https://www.ncbi.nlm.nih.gov/pubmed/18842774. | Daily Eating Occasions Not Reported
322 | Gnanou JV, Caszo BA, Khalil KM, Abdullah SL, Knight VF, Bidin MZ. Effects of Ramadan fasting on glucose homeostasis and adiponectin levels in healthy adult males. J Diabetes Metab Disord. 2015. 14:55 https://www.ncbi.nlm.nih.gov/pubmed/26155596 | Daily Eating Occasions Not Reported
323 | Godfrey JR, Dansinger ML. Toward optimal health: sorting out the dietary approaches to achieve a healthy weight. J Womens Health (Larchmt). 2009. 18:435–8 https://www.ncbi.nlm.nih.gov/pubmed/19361308 | Study Design
324 | Godlin Jeneta J, Preetha. Effect of breakfast in body mass index among college going students. Journal of pharmaceutical sciences and research. 2016. 8:545–551 | Intervention/Exposure, Daily Eating Occasions Not Reported
325 | Goel N, Hopkins C, Ruggieri M, Ahima RS, Allison KC. Delayed eating adversely impacts weight and metabolism compared with daytime eating in normal weight adults. Sleep. 2017. 40:A24–A25 | Study Design, Publication Status
326 | Goel N, Hopkins C, Ruggieri M, Zhang Z, Taylor DM, Allison KC. The impact of nighttime eating: a randomized controlled trial of daytime vs. delayed eating on weight and metabolism in adults of normal weight. Sleep. 2019. 42:A15 | Study Design, Publication Status
327 | Goel N, Stunkard AJ, Rogers NL, Van Dongen HP, Allison KC, O’Reardon JP, Ahima RS, Cummings DE, Heo M, Dinges DF. Circadian rhythm profiles in women with night eating syndrome. J Biol Rhythms. 2009. 24:85–94 https://www.ncbi.nlm.nih.gov/pubmed/19150931 | Daily Eating Occasions Not Reported
328 | Goff LM, Huang P, Silva MJ, Bordoli C, Enayat EZ, Molaodi OR, Cassidy A, Maynard M, Harding S. Associations of dietary intake with cardiometabolic risk in a multi-ethnic cohort: a longitudinal analysis of the Determinants of Adolescence, now young Adults, Social well-being and Health (DASH) study. Br J Nutr. 2019. 121:1069–1079 https://www.ncbi.nlm.nih.gov/pubmed/30764887 | Daily Eating Occasions Not Reported, Eating Frequency Data Collection
329 | Goldhamer AC, Lisle DJ, Sultana P, Anderson SV, Parpia B, Hughes B, Campbell TC. Medically supervised water-only fasting in the treatment of borderline hypertension. J Altern Complement Med. 2002. 8:643–50 https://www.ncbi.nlm.nih.gov/pubmed/12470446 | Intervention/Exposure, Daily Eating Occasions Not Reported
330 | Gonzalez JT, Richardson JD, Chowdhury EA, Koumanov F, Holman GD, Cooper S, Thompson D, Tsintzas K, Betts JA. Molecular adaptations of adipose tissue to 6 weeks of morning fasting vs. daily breakfast consumption in lean and obese adults. J Physiol. 2018. 596:609–622 https://www.ncbi.nlm.nih.gov/pubmed/29193093 | Intervention/Exposure, Daily Eating Occasions Not Reported, Size of Study Groups
331 | Gonzalez-Gonzalez A, Betancourt-Ocampo D, Tavel-Gelrud D, Martinez-Lanz P. Risk eating behaviors in male and female students: a longitudinal study. Eat Behav. 2014. 15:252–4 https://www.ncbi.nlm.nih.gov/pubmed/24854813 | Intervention/Exposure
332 | Gordon-Larsen P, Heymsfield SB. Obesity as a Disease, Not a Behavior. Circulation. 2018. 137:1543–1545 https://www.ncbi.nlm.nih.gov/pubmed/29632150 | Study Design
333 | Gorin AA, Phelan S, Wing RR, Hill JO. Promoting long-term weight control: does dieting consistency matter?. Int J Obes Relat Metab Disord. 2004. 28:278–81 https://www.ncbi.nlm.nih.gov/pubmed/14647183 | Intervention/Exposure, Daily Eating Occasions Not Reported
334 | Goto M, Kiyohara K, Kawamura T. Lifestyle risk factors for overweight in Japanese male college students. Public Health Nutr. 2010. 13:1575–80 https://www.ncbi.nlm.nih.gov/pubmed/20025829 | Intervention/Exposure, Daily Eating Occasions Not Reported
335 | Goyal R, Julka S. Impact of breakfast skipping on the health status of the population. Indian J Endocrinol Metab. 2014. 18:683–7 https://www.ncbi.nlm.nih.gov/pubmed/25285286 | Study Design, Daily Eating Occasions Not Reported
336 | Grant C, Coates A, Dorrian J, Kennaway D, Wittert G, Heilbronn L, et al. Eating on simulated night shift effects glucose response to breakfast: pilot study. FASEB journal. 2016;30 | Study Design, Publication Status
337 | Grant C, Coates A, Dorrian J, Kennaway D, Wittert G, Heilbronn L, Pajcin M, Della Vedova C, Gupta C, Banks S. Fasting during night shift: a strategy to reduce the metabolic impact of shift-work. Sleep. 2016. 39:A51 | Publication Status
338 | Grant CL, Coates AM, Dorrian J, Kennaway DJ, Wittert GA, Heilbronn LK, Pajcin M, Della Vedova C, Gupta CC, Banks S. Timing of food intake during simulated night shift impacts glucose metabolism: A controlled study. Chronobiol Int. 2017. 34:1003–1013 https://www.ncbi.nlm.nih.gov/pubmed/28635334 | Intervention/Exposure, Daily Eating Occasions Not Reported, Comparator
339 | Gray-Donald K, Robinson E, Collier A, David K, Renaud L, Rodrigues S. Intervening to reduce weight gain in pregnancy and gestational diabetes mellitus in Cree communities: an evaluation. Cmaj. 2000. 163:1247–51 https://www.ncbi.nlm.nih.gov/pubmed/11107459 | Intervention/Exposure
340 | Grilo CM, Masheb RM. Night-time eating in men and women with binge eating disorder. Behav Res Ther. 2004. 42:397–407 https://www.ncbi.nlm.nih.gov/pubmed/14998734 | Health Status
341 | Gueldich H, Zghal F, Borji R, Chtourou H, Sahli S, Rebai H. The effects of Ramadan intermittent fasting on the underlying mechanisms of force production capacity during maximal isometric voluntary contraction. Chronobiol Int. 2019. 36:698–708 https://www.ncbi.nlm.nih.gov/pubmed/30889992 | Daily Eating Occasions Not Reported
342 | Guelinckx I, Devlieger R, Mullie P, Vansant G. Effect of lifestyle intervention on dietary habits, physical activity, and gestational weight gain in obese pregnant women: a randomized controlled trial. Am J Clin Nutr. 2010. 91:373–80 https://www.ncbi.nlm.nih.gov/pubmed/19955397 | Intervention/Exposure
343 | Guinter MA, Park YM, Steck SE, Sandler DP. Day-to-day regularity in breakfast consumption is associated with weight status in a prospective cohort of women. Int J Obes (Lond). 2019;44(1):186–94. https://www.ncbi.nlm.nih.gov/pubmed/30926951. | Daily Eating Occasions Not Reported
344 | Gupta CC, Centofanti S, Dorrian J, Coates AM, Stepien JM, Kennaway D, et al. Subjective Hunger, Gastric Upset, and Sleepiness in Response to Altered Meal Timing during Simulated Shiftwork. Nutrients. 2019;11(6). https://www.ncbi.nlm.nih.gov/pubmed/31208092. | Comparator, Outcome
345 | Gupta M, Khajuria V, Akhter P. Effects of ramadan fasting on cardiovascular and biochemical parameters. Indian Journal of Community Health. 2013. 25:460–464 | Daily Eating Occasions Not Reported
346 | Gur EB, Turan GA, Ince O, Karadeniz M, Tatar S, Kasap E, Sahin N, Guclu S. Effect of Ramadan fasting on metabolic markers, dietary intake and abdominal fat distribution in pregnancy. Hippokratia. 2015. 19:298–303 https://www.ncbi.nlm.nih.gov/pubmed/27688692 | Intervention/Exposure, Daily Eating Occasions Not Reported
347 | Gwin JA, Leidy HJ. A pilot study assessing whether the consumption of a protein-rich breakfast improves appetite control, eating behavior, and sleep quality compared to skipping breakfast in healthy young professionals. Sleep. 2017. 40:A300 | Study Design, Publication Status
348 | Gwin JA, Leidy HJ. Breakfast Consumption Augments Appetite, Eating Behavior, and Exploratory Markers of Sleep Quality Compared with Skipping Breakfast in Healthy Young Adults. Curr Dev Nutr. 2018. 2:nzy074 https://www.ncbi.nlm.nih.gov/pubmed/30402594 | Outcome, Size of Study Groups
349 | Ha SA, Lee SY, Kim KA, Seo JS, Sohn CM, Park HR, Kim KW. Eating habits, physical activity, nutrition knowledge, and self-efficacy by obesity status in upper-grade elementary school students. Nutr Res Pract. 2016. 10:597–605 https://www.ncbi.nlm.nih.gov/pubmed/27909557 | Study Design
350 | Haakstad LA, Voldner N, Bo K. Attitudes and awareness towards weight gain among normal weight and overweight pregnant women. J Matern Fetal Neonatal Med. 2015. 28:1569–74 https://www.ncbi.nlm.nih.gov/pubmed/25184626 | Intervention/Exposure
351 | Haas K, Hayoz S, Maurer-Wiesner S. Effectiveness and Feasibility of a Remote Lifestyle Intervention by Dietitians for Overweight and Obese Adults: Pilot Study. JMIR Mhealth Uhealth. 2019. 7:e12289 https://www.ncbi.nlm.nih.gov/pubmed/30973338 | Intervention/Exposure
352 | Haerens L, Vereecken C, Maes L, De Bourdeaudhuij I. Relationship of physical activity and dietary habits with body mass index in the transition from childhood to adolescence: a 4-year longitudinal study. Public Health Nutr. 2010. 13:1722–8 https://www.ncbi.nlm.nih.gov/pubmed/20883572 | Daily Eating Occasions Not Reported
353 | Hager ER, Calamaro CJ, Bentley LM, Hurley KM, Wang Y, Black MM. Nighttime Sleep Duration and Sleep Behaviors among Toddlers from Low-Income Families: Associations with Obesogenic Behaviors and Obesity and the Role of Parenting. Child Obes. 2016. 12:392–400 https://www.ncbi.nlm.nih.gov/pubmed/27447782 | Study Design, Intervention/Exposure
354 | Haghdoost AA, Poorranjbar M. The interaction between physical activity and fasting on the serum lipid profile during Ramadan. Singapore Med J. 2009. 50:897–901 https://www.ncbi.nlm.nih.gov/pubmed/19787180 | Intervention/Exposure, Daily Eating Occasions Not Reported
355 | Haines J, Stang J. Promoting meal consumption among teens. J Am Diet Assoc. 2005. 105:945–7 https://www.ncbi.nlm.nih.gov/pubmed/15942546 | Study Design, Publication Status
356 | Hajek P, Myers K, Dhanji AR, West O, McRobbie H. Weight change during and after Ramadan fasting. J Public Health (Oxf). 2012. 34:377–81 https://www.ncbi.nlm.nih.gov/pubmed/22083256 | Daily Eating Occasions Not Reported
357 | Halberg N, Henriksen M, Soderhamn N, Stallknecht B, Ploug T, Schjerling P, Dela F. Effect of intermittent fasting and refeeding on insulin action in healthy men. J Appl Physiol. 2005. 99:2128–36 https://www.ncbi.nlm.nih.gov/pubmed/16051710 | Daily Eating Occasions Not Reported, Size of Study Groups
358 | Halsey LG, Huber JW, Low T, Ibeawuchi C, Woodruff P, Reeves S. Does consuming breakfast influence activity levels? An experiment into the effect of breakfast consumption on eating habits and energy expenditure. Public Health Nutr. 2012. 15:238–45 https://www.ncbi.nlm.nih.gov/pubmed/21729464 | Intervention/Exposure, Daily Eating Occasions Not Reported
359 | Haluzik M, Matoulek M, Svacina S, Hilgertova J, Haas T. The influence of short-term fasting on serum leptin levels, and selected hormonal and metabolic parameters in morbidly obese and lean females. Endocr Res. 2001. 27:251–60 https://www.ncbi.nlm.nih.gov/pubmed/11428717 | Intervention/Exposure, Daily Eating Occasions Not Reported
360 | Hamed IM, Hussein MM, El-Damhougy ST. The effect of the Coptic Orthodox Christian fasting on dietary intake and some biochemical parameters. Research Journal of Pharmaceutical, Biological and Chemical Sciences. 2016. 7:539–543 | Intervention/Exposure, Daily Eating Occasions Not Reported, Publication Status
361 | Hamermesh DS. Incentives, time use and BMI: The roles of eating, grazing and goods. Econ Hum Biol. 2010. 8:2–15 Study Design, Daily Eating https://www.ncbi.nlm.nih.gov/pubmed/20079698 | Occasions Not Reported
362 | Hammouda O, Chtourou H, Aloui A, Chahed H, Kallel C, Miled A, Chamari K, Chaouachi A, Souissi N. Concomitant effects of Ramadan fasting and time-of-day on apolipoprotein AI, B, Lp-a and homocysteine responses during aerobic exercise in Tunisian soccer players. PLoS One. 2013. 8:e79873 https://www.ncbi.nlm.nih.gov/pubmed/24244572 | Daily Eating Occasions Not Reported
363 | Hampl JS, Heaton CL, Taylor CA. Snacking patterns influence energy and nutrient intakes but not body mass index. J Hum Nutr Diet. 2003. 16:3–11 https://www.ncbi.nlm.nih.gov/pubmed/12581404 | Study Design
364 | Haouari M, Haouari-Oukerro F, Sfaxi A, Ben Rayana MC, Kaabachi N, Mbazaa A. How Ramadan fasting affects caloric consumption, body weight, and circadian evolution of cortisol serum levels in young, healthy male volunteers. Horm Metab Res. 2008. 40:575–7 https://www.ncbi.nlm.nih.gov/pubmed/18393168 | Daily Eating Occasions Not Reported
365 | Harder-Lauridsen NM, Nielsen ST, Mann SP, Lyngbaek MP, Benatti FB, Langkilde AR, Law I, Wedell-Neergaard AS, Thomsen C, Moller K, Karstoft K, Pedersen BK, Krogh-Madsen R. The effect of alternate-day caloric restriction on the metabolic consequences of 8 days of bed rest in healthy lean men: a randomized trial. J Appl Physiol. 2017. 122:230–241 https://www.ncbi.nlm.nih.gov/pubmed/27881670 | Daily Eating Occasions Not Reported, Publication Date
366 | Harder-Lauridsen NM, Rosenberg A, Benatti FB, Damm JA, Thomsen C, Mortensen EL, Pedersen BK, KroghMadsen R. Ramadan model of intermittent fasting for 28 d had no major effect on body composition, glucose metabolism, or cognitive functions in healthy lean men. Nutrition. 2017. 37:92–103 https://www.ncbi.nlm.nih.gov/pubmed/28359370 | Daily Eating Occasions Not Reported, Size of Study Groups
367 | Hart CN, Carskadon MA, Demos KE, Van Reen E, Sharkey KM, Raynor HA, Considine RV, Jones RN, Wing RR. Acute Changes in Sleep Duration on Eating Behaviors and Appetite-Regulating Hormones in Overweight/Obese Adults. Behav Sleep Med. 2015. 13:424–36 https://www.ncbi.nlm.nih.gov/pubmed/25105727 | Intervention/Exposure
368 | Hartline-Grafton HL, Rose D, Johnson CC, Rice JC, Webber LS. The influence of weekday eating patterns on energy intake and BMI among female elementary school personnel. Obesity (Silver Spring). 2010. 18:736–42 https://www.ncbi.nlm.nih.gov/pubmed/19696760 | Study Design
369 | Harvey J, Howell A, Morris J, Harvie M. Intermittent energy restriction for weight loss: Spontaneous reduction of Daily Eating Occasions Not energy intake on unrestricted days. Food Sci Nutr. 2018. 6:674–680 https://www.ncbi.nlm.nih.gov/pubmed/29876119 | Reported
370 | Harvie M, Wright C, Pegington M, McMullan D, Mitchell E, Martin B, Cutler RG, Evans G, Whiteside S, Maudsley S, Camandola S, Wang R, Carlson OD, Egan JM, Mattson MP, Howell A. The effect of intermittent energy and carbohydrate restriction v. daily energy restriction on weight loss and metabolic disease risk markers in overweight women. Br J Nutr. 2013. 110:1534–47 https://www.ncbi.nlm.nih.gov/pubmed/23591120 | Intervention/Exposure, Daily Eating Occasions Not Reported
371 | Harvie MN, Sims AH, Pegington M, Spence K, Mitchell A, Vaughan AA, Allwood JW, Xu Y, Rattray NJ, Goodacre R, Evans DG, Mitchell E, McMullen D, Clarke RB, Howell A. Intermittent energy restriction induces changes in breast gene expression and systemic metabolism. Breast Cancer Res. 2016. 18:57 https://www.ncbi.nlm.nih.gov/pubmed/27233359 | Daily Eating Occasions Not Reported
372 | Hassan BK, Cunha DB, da Veiga GV, Pereira RA, Sichieri R. Changes in breakfast frequency and composition during adolescence: The Adolescent Nutritional Assessment Longitudinal Study, a cohort from Brazil. PLoS One. 2018. 13:e0200587 https://www.ncbi.nlm.nih.gov/pubmed/30024906 | Study Design
373 | Hassan NE, El Shebini SM, Ahmed NH. Association between Dietary Patterns, Breakfast Skipping and Familial Obesity among a Sample of Egyptian Families. Open Access Maced J Med Sci. 2016. 4:213–8 https://www.ncbi.nlm.nih.gov/pubmed/27335589 | Study Design
374 | Hatami Zargaran Z, Salehi M, Heydari ST, Babajafari S. The Effects of 6 Isocaloric Meals on Body Weight, Lipid Profiles, Leptin, and Adiponectin in Overweight Subjects (BMI > 25). Int Cardiovasc Res J. 2014. 8:52–6 https://www.ncbi.nlm.nih.gov/pubmed/24936481 | Daily Eating Occasions Not Reported, Eating Frequency Data Collection
375 | Haus E, Reinberg A, Mauvieux B, Le Floc’h N, Sackett-Lundeen L, Touitou Y. Risk of obesity in male shift workers: A chronophysiological approach. Chronobiol Int. 2016. 33:1018–36 https://www.ncbi.nlm.nih.gov/pubmed/27366928 | Intervention/Exposure
376 | He F, Bixler EO, Berg A, Imamura Kawasawa Y, Vgontzas AN, Fernandez-Mendoza J, et al. Habitual sleep variability, not sleep duration, is associated with caloric intake in adolescents. Sleep medicine. 2015;16(7):856–61. https://www.ncbi.nlm.nih.gov/pubmed/26002758. | Study Design
377 | He F, Zuo L, Emery W, Arciero P. High protein intermittent fasting increases serum polychlorinated biphenyls and decreases oxidative stress in obese adults. Journal of hypertension. 2017. 35:e258 | Publication Status
378 | Headland M, Clifton P, Keogh J. Intermittent compared to continuous energy restriction on weight loss and weight maintenance: effects after 12 months. Obesity research & clinical practice. 2019. 13:268–269 | Publication Status
379 | Headland ML, Clifton PM, Keogh JB. Effect of intermittent compared to continuous energy restriction on weight loss and weight maintenance after 12 months in healthy overweight or obese adults. Int J Obes (Lond). 2018;43(10):2028–36. https://www.ncbi.nlm.nih.gov/pubmed/30470804. | Daily Eating Occasions Not Reported
380 | Headland ML, Clifton PM, Keogh JB. Effect of Intermittent Energy Restriction on Flow Mediated Dilatation, a Measure of Endothelial Function: A Short Report. Int J Environ Res Public Health. 2018;15(6). https://www.ncbi.nlm.nih.gov/pubmed/29867034. | Intervention/Exposure, Daily Eating Occasions Not Reported
381 | Heart failure. J Pract Nurs. 2008. 58:20–5 https://www.ncbi.nlm.nih.gov/pubmed/19260364 | Study Design
382 | Heden TD, Liu Y, Sims LJ, Whaley-Connell AT, Chockalingam A, Dellsperger KC, Kanaley JA. Meal frequency differentially alters postprandial triacylglycerol and insulin concentrations in obese women. Obesity (Silver Spring). 2013. 21:123–9 https://www.ncbi.nlm.nih.gov/pubmed/23505176 | Size of Study Groups
383 | Heery E, Kelleher CC, Wall PG, McAuliffe FM. Prediction of gestational weight gain - a biopsychosocial model. Public Health Nutr. 2015. 18:1488–98 https://www.ncbi.nlm.nih.gov/pubmed/25171690 | Daily Eating Occasions Not Reported
384 | Heery E, Wall PG, Kelleher CC, McAuliffe FM. Effects of dietary restraint and weight gain attitudes on gestational weight gain. Appetite. 2016. 107:501–510 https://www.ncbi.nlm.nih.gov/pubmed/27545671 | Intervention/Exposure
385 | Heilbronn LK, Civitarese AE, Bogacka I, Smith SR, Hulver M, Ravussin E. Glucose tolerance and skeletal muscle gene expression in response to alternate day fasting. Obes Res. 2005. 13:574–81 https://www.ncbi.nlm.nih.gov/pubmed/15833943 | Daily Eating Occasions Not Reported, Size of Study Groups
386 | Heilbronn LK, Smith SR, Martin CK, Anton SD, Ravussin E. Alternate-day fasting in nonobese subjects: effects on body weight, body composition, and energy metabolism. Am J Clin Nutr. 2005. 81:69–73 https://www.ncbi.nlm.nih.gov/pubmed/15640462 | Daily Eating Occasions Not Reported, Size of Study Groups
387 | Helle C, Hillesund ER, Wills AK, Overby NC. Evaluation of an eHealth intervention aiming to promote healthy food habits from infancy -the Norwegian randomized controlled trial Early Food for Future Health. Int J Behav Nutr Phys Act. 2019. 16:1 https://www.ncbi.nlm.nih.gov/pubmed/30606197 | Age: Intervention/Exposure
388 | Hennessy MD, Volpe SL, Sammel MD, Gennaro S. Skipping meals and less walking among African Americans diagnosed with preterm labor. J Nurs Scholarsh. 2010. 42:147–55 https://www.ncbi.nlm.nih.gov/pubmed/20618599 | Outcome
389 | Heriseanu AI, Hay P, Touyz S. The short inventory of grazing (SIG): development and validation of a new brief measure of a common eating behaviour with a compulsive dimension. J Eat Disord. 2019. 7:4 https://www.ncbi.nlm.nih.gov/pubmed/30774954 | Intervention/Exposure
390 | Herman CP, van Strien T, Polivy J. Undereating or eliminating overeating?. Am Psychol. 2008. 63:202–3 https://www.ncbi.nlm.nih.gov/pubmed/18377113 | Intervention/Exposure
391 | Hermenegildo Y, Lopez-Garcia E, Garcia-Esquinas E, Perez-Tasigchana RF, Rodriguez-Artalejo F, Guallar-Castillon P. Distribution of energy intake throughout the day and weight gain: a population-based cohort study in Spain. Br J Nutr. 2016. 115:2003–10 https://www.ncbi.nlm.nih.gov/pubmed/27044416 | Intervention/Exposure
392 | Heron KE, Scott SB, Sliwinski MJ, Smyth JM. Eating behaviors and negative affect in college women’s everyday lives. Int J Eat Disord. 2014. 47:853–9 https://www.ncbi.nlm.nih.gov/pubmed/24797029 | Intervention/Exposure
393 | Herrmann TS, Siega-Riz AM, Hobel CJ, Aurora C, Dunkel-Schetter C. Prolonged periods without food intake during pregnancy increase risk for elevated maternal corticotropin-releasing hormone concentrations. Am J Obstet Gynecol. 2001. 185:403–12 https://www.ncbi.nlm.nih.gov/pubmed/11518900 | Intervention/Exposure, Daily Eating Occasions Not Reported
394 | Hibi M, Hari S, Yamaguchi T, Mitsui Y, Kondo S, Katashima M. Effect of Short-Term Increase in Meal Frequency on Glucose Metabolism in Individuals with Normal Glucose Tolerance or Impaired Fasting Glucose: A Randomized Crossover Clinical Trial. Nutrients. 2019;11(9). https://www.ncbi.nlm.nih.gov/pubmed/31489910. | Size of Study Groups
395 | Hibi M, Katashima M, Tokuyama K, Satoh M. Effect of meal frequency on 24-h blood glucose profiles assessed with continuous glucose monitoring in subjects with normal and impaired fasting glucose tolerance. Diabetes. 2012. 61:A187 | Study Design, Publication Status
396 | Hibi M, Kubota C, Mizuno T, Aritake S, Mitsui Y, Katashima M, Uchida S. Effect of shortened sleep on energy expenditure, core body temperature, and appetite: a human randomised crossover trial. Sci Rep. 2017. 7:39640 https://www.ncbi.nlm.nih.gov/pubmed/28071649 | Comparator
397 | Hibi M, Masumoto A, Naito Y, Kiuchi K, Yoshimoto Y, Matsumoto M, Katashima M, Oka J, Ikemoto S. Nighttime snacking reduces whole body fat oxidation and increases LDL cholesterol in healthy young women. Am J Physiol Regul Integr Comp Physiol. 2013. 304:R94–r101 https://www.ncbi.nlm.nih.gov/pubmed/23174861 | Daily Eating Occasions Not Reported, Size of Study Groups
398 | Higashikawa A, Suwazono Y, Okubo Y, Uetani M, Kobayashi E, Kido T, Nogawa K. Association of working conditions and lifestyle with increased serum gamma-glutamyltransferase: a follow-up study. Arch Med Res. 2005. 36:567–73 https://www.ncbi.nlm.nih.gov/pubmed/16099340 | Outcome
399 | High blood pressure. J Pract Nurs. 2008. 58:9–14 https://www.ncbi.nlm.nih.gov/pubmed/19260362 | Study Design
400 | Hinton PS, Olson CM. Postpartum exercise and food intake: the importance of behavior-specific self-efficacy. J Am Diet Assoc. 2001. 101:1430–7 https://www.ncbi.nlm.nih.gov/pubmed/11762738 | Outcome
401 | Hirschler V, Buzzano K, Erviti A, Ismael N, Silva S, Dalamon R. Overweight and lifestyle behaviors of low socioeconomic elementary school children in Buenos Aires. BMC Pediatr. 2009. 9:17 https://www.ncbi.nlm.nih.gov/pubmed/19239682 | Study Design
402 | Hirsh SP, Pons M, Joyal SV, Swick AG. Avoiding holiday seasonal weight gain with nutrient-supported intermittent energy restriction: a pilot study. J Nutr Sci. 2019. 8:e11 https://www.ncbi.nlm.nih.gov/pubmed/30931109 | Daily Eating Occasions Not Reported
403 | Hizli D, Yilmaz SS, Onaran Y, Kafali H, Danisman N, Mollamahmutoglu L. Impact of maternal fasting during Ramadan on fetal Doppler parameters, maternal lipid levels and neonatal outcomes. J Matern Fetal Neonatal Med. 2012. 25:975–7 https://www.ncbi.nlm.nih.gov/pubmed/21740320 | Study Design, Daily Eating Occasions Not Reported
404 | Hjorth MF, Quist JS, Andersen R, Michaelsen KF, Tetens I, Astrup A, Chaput JP, Sjodin A. Change in sleep duration and proposed dietary risk factors for obesity in Danish school children. Pediatr Obes. 2014. 9:e156–9 https://www.ncbi.nlm.nih.gov/pubmed/25251317 | Intervention/Exposure
405 | Hjorth MF, Sjodin A, Dalskov SM, Damsgaard CT, Michaelsen KF, Biltoft-Jensen A, Andersen R, Ritz C, Chaput JP, Astrup A. Sleep duration modifies effects of free ad libitum school meals on adiposity and blood pressure. Appl Physiol Nutr Metab. 2016. 41:33–40 https://www.ncbi.nlm.nih.gov/pubmed/26647154 | Intervention/Exposure
406 | Hoddy K, Kroeger C, Trepanowski J, Bhutani S, Barnosky A, Varady K. Meal timing during alternate day fasting: effects on body weight and coronary heart disease risk in obese adults. FASEB journal. 2014;28(Suppl. 1) | Study Design, Publication Status
407 | Hoddy KK, Bhutani S, Phillips SA, Varady KA. Effects of different degrees of insulin resistance on endothelial function in obese adults undergoing alternate day fasting. Nutr Healthy Aging. 2016. 4:63–71 https://www.ncbi.nlm.nih.gov/pubmed/28035343 | Daily Eating Occasions Not Reported
408 | Hoddy KK, Kroeger CM, Trepanowski JF, Barnosky A, Bhutani S, Varady KA. Meal timing during alternate day fasting: Impact on body weight and cardiovascular disease risk in obese adults. Obesity (Silver Spring). 2014. 22:2524–31 https://www.ncbi.nlm.nih.gov/pubmed/25251676 | Eating Frequency Data Collection
409 | Hoddy KK, Kroeger CM, Trepanowski JF, Barnosky AR, Bhutani S, Varady KA. Safety of alternate day fasting and effect on disordered eating behaviors. Nutr J. 2015. 14:44 https://www.ncbi.nlm.nih.gov/pubmed/25943396 | Intervention/Exposure, Daily Eating Occasions Not Reported, Outcome
410 | Hoffmann DA, Carels RA. Does when you eat and exercise matter? Differences in eating and physical activity patterns in overweight and obese adults. Eat Weight Disord. 2016. 21:91–8 https://www.ncbi.nlm.nih.gov/pubmed/26286898 | Intervention/Exposure
411 | Hofmann W, Adriaanse M, Vohs KD, Baumeister RF. Dieting and the self-control of eating in everyday environments: an experience sampling study. Br J Health Psychol. 2014. 19:523–39 https://www.ncbi.nlm.nih.gov/pubmed/23751109 | Intervention/Exposure, Daily Eating Occasions Not Reported
412 | Hojlund K, Wildner-Christensen M, Eshoj O, Skjaerbaek C, Holst JJ, Koldkjaer O, Moller Jensen D, Beck-Nielsen H. Reference intervals for glucose, beta-cell polypeptides, and counterregulatory factors during prolonged fasting. Am J Physiol Endocrinol Metab. 2001. 280:E50–8 https://www.ncbi.nlm.nih.gov/pubmed/11120658 | Study Design, Intervention/Exposure, Daily Eating Occasions Not Reported
413 | Holmback I, Ericson U, Gullberg B, Wirfalt E. Five meal patterns are differently associated with nutrient intakes, lifestyle factors and energy misreporting in a sub-sample of the Malmo Diet and Cancer cohort. Food Nutr Res. 2009; 53:1–16. https://www.ncbi.nlm.nih.gov/pubmed/19798420. | Study Design
414 | Holmback U, Lowden A, Akerfeldt T, Lennernas M, Hambraeus L, Forslund J, Akerstedt T, Stridsberg M, Forslund A. The human body may buffer small differences in meal size and timing during a 24-h wake period provided energy balance is maintained. J Nutr. 2003. 133:2748–55 https://www.ncbi.nlm.nih.gov/pubmed/12949360 | Size of Study Groups
415 | Holmback U. Metabolic, endocrine and mood responses to nocturnal eating in men are affected by sources of dietary energy. Ups J Med Sci. 2002. 107:121–58 https://www.ncbi.nlm.nih.gov/pubmed/12696573 | Study Design
416 | Holmstrup ME, Owens CM, Fairchild TJ, Kanaley JA. Effect of meal frequency on glucose and insulin excursions over the course of a day. e-SPEN. 2010. 5:e277–e280 | Size of Study Groups
417 | Hopkins LC, Sattler M, Steeves EA, Jones-Smith JC, Gittelsohn J. Breakfast Consumption Frequency and Its Study Design, Daily Eating Relationships to Overall Diet Quality, Using Healthy Eating Index 2010, and Body Mass Index among Adolescents in Occasions Not Reported a Low-Income Urban Setting. Ecol Food Nutr. 2017. 56:297–311 https://www.ncbi.nlm.nih.gov/pubmed/28604287 | Study Design, Daily Eating Occasions Not Reported
418 | Horne BD, May HT, Anderson JL, Kfoury AG, Bailey BM, McClure BS, Renlund DG, Lappe DL, Carlquist JF, Fisher PW, Pearson RR, Bair TL, Adams TD, Muhlestein JB. Usefulness of routine periodic fasting to lower risk of coronary artery disease in patients undergoing coronary angiography. Am J Cardiol. 2008. 102:814–819 https://www.ncbi.nlm.nih.gov/pubmed/18805103 | Study Design, Daily Eating Occasions Not Reported
419 | Horne BD, Muhlestein JB, Lappe DL, May HT, Carlquist JF, Galenko O, Brunisholz KD, Anderson JL. Randomized Intervention/Exposure, Daily cross-over trial of short-term water-only fasting: metabolic and cardiovascular consequences. Nutr Metab Eating Occasions Not Reported Cardiovasc Dis. 2013. 23:1050–7 https://www.ncbi.nlm.nih.gov/pubmed/23220077 | Intervention/Exposure, Daily Eating Occasions Not Reported
420 | Horne BD, Muhlestein JB, May HT, Carlquist JF, Lappe DL, Bair TL, Anderson JL. Relation of routine, periodic fasting to risk of diabetes mellitus, and coronary artery disease in patients undergoing coronary angiography. Am J Cardiol. 2012. 109:1558–62 https://www.ncbi.nlm.nih.gov/pubmed/22425331 | Intervention/Exposure, Daily Eating Occasions Not Reported
421 | Horne BD. Is periodic fasting really good for reducing cardiovascular risk and improving heart health? Future Cardiology. 2011;7(6):721–4. https://www.ncbi.nlm.nih.gov/pubmed/22050055. | Study Design, Publication Status
422 | Horowitz JF, Coppack SW, Klein S. Whole-body and adipose tissue glucose metabolism in response to short-term fasting in lean and obese women. Am J Clin Nutr. 2001. 73:517–22 https://www.ncbi.nlm.nih.gov/pubmed/11237926 | Intervention/Exposure, Daily Eating Occasions Not Reported, Comparator
423 | Huang TT, Howarth NC, Lin BH, Roberts SB, McCrory MA. Energy intake and meal portions: associations with BMI percentile in U.S. children. Obes Res. 2004. 12:1875–85 https://www.ncbi.nlm.nih.gov/pubmed/15601985 | Study Design
424 | Hughes S, Dennison CR. Progress in prevention: economic downturn = cardiovascular disease risk uptick?. J Cardiovasc Nurs. 2009. 24:287–9 https://www.ncbi.nlm.nih.gov/pubmed/21206351 | Study Design
425 | Hui A, Back L, Ludwig S, Gardiner P, Sevenhuysen G, Dean H, Sellers E, McGavock J, Morris M, Bruce S, etal. Lifestyle intervention on diet and exercise reduced excessive gestational weight gain in pregnant women under a randomized controlled trial. Obstetrical & gynecological survey. 2012. 67:263–264 | Study Design, Publication Status
426 | Hulman A, Faerch K, Vistisen D, Karsai J, Nyari TA, Tabak AG, Brunner EJ, Kivimaki M, Witte DR. Effect of time of day and fasting duration on measures of glycaemia: analysis from the Whitehall II Study. Diabetologia. 2013. 56:294–7 https://www.ncbi.nlm.nih.gov/pubmed/23143165 | Intervention/Exposure
427 | Hume DJ, Kroff J, Clamp LD, Lambert EV. Compensations for Weight Loss in Successful and Unsuccessful Dieters. Intervention/Exposure Am J Health Behav. 2015. 39:589–600 https://www.ncbi.nlm.nih.gov/pubmed/26248169 | Intervention/Exposure
428 | Huseinovic E, Winkvist A, Freisling H, Slimani N, Boeing H, Buckland G, Schwingshackl L, Olsen A, Tjonneland A, Stepien M, Boutron-Ruault MC, Mancini F, Artaud F, Kuhn T, Katzke V, Trichopoulou A, Naska A, Orfanos P, Tumino R, Masala G, Krogh V, Santucci de Magistris M, Ocke MC, Brustad M, Jensen TE, Skeie G, Rodriguez-Barranco M, Huerta JM, Ardanaz E, Quiros JR, Jakszyn P, Sonestedt E, Ericson U, Wennberg M, Key TJ, Aune D, Riboli E, Weiderpass E, Berteus Forslund H. Timing of eating across ten European countries - results from the European Prospective Investigation into Cancer and Nutrition (EPIC) calibration study. Public Health Nutr. 2019. 22:324–335 https://www.ncbi.nlm.nih.gov/pubmed/30326988 | Study Design
429 | Hussin NM, Shahar S, Teng NI, Ngah WZ, Das SK. Efficacy of fasting and calorie restriction (FCR) on mood and depression among ageing men. J Nutr Health Aging. 2013. 17:674–80 https://www.ncbi.nlm.nih.gov/pubmed/24097021 | Intervention/Exposure, Daily Eating Occasions Not Reported, Size of Study Groups
430 | Hutchison AT, Liu B, Wittert GA, Heilbronn LK. Effects of intermittent fasting, with and without calorie restriction, on human metabolic health. Obesity reviews. 2016. 17:54 | Publication Status
431 | Hutchison AT, Liu B, Wood RE, Vincent AD, Thompson CH, O’Callaghan NJ, Wittert GA, Heilbronn LK. Effects of Intermittent Versus Continuous Energy Intakes on Insulin Sensitivity and Metabolic Risk in Women with Overweight. Obesity (Silver Spring). 2019. 27:50–58 https://www.ncbi.nlm.nih.gov/pubmed/30569640 | Daily Eating Occasions Not Reported, Size of Study Groups
432 | Hutchison AT, Regmi P, Manoogian ENC, Fleischer JG, Wittert GA, Panda S, Heilbronn LK. Time-Restricted Feeding Improves Glucose Tolerance in Men at Risk for Type 2 Diabetes: A Randomized Crossover Trial. Obesity (Silver Spring). 2019. 27:724–732 https://www.ncbi.nlm.nih.gov/pubmed/31002478 | Daily Eating Occasions Not Reported, Comparator
433 | Hyzyk AK, Reguła J, Jeszka J. Evaluation of total energy balance and food habits of obese children. Medycyna wieku rozwojowego. 2000;4(2):109–18. https://www.ncbi.nlm.nih.gov/pubmed/11013866. | Language
434 | Ibe Y, Miyakawa H, Fuse-Nagase Y, Hirose AS, Hirasawa R, Yachi Y, Fujihara K, Kobayashi K, Shimano H, Sone H. Association of eating three meals irregularly with changes in BMI and weight among young Japanese men and women: A 2-year follow-up. Physiol Behav. 2016. 163:81–87 https://www.ncbi.nlm.nih.gov/pubmed/27126967 | Daily Eating Occasions Not Reported
435 | Ibrahim WH, Habib HM, Jarrar AH, Al Baz SA. Effect of Ramadan fasting on markers of oxidative stress and serum biochemical markers of cellular damage in healthy subjects. Ann Nutr Metab. 2008. 53:175–81 https://www.ncbi.nlm.nih.gov/pubmed/19011280 | Daily Eating Occasions Not Reported
436 | Ibrahim WH, Habib HM, Jarrar AH, Al Baz SA. Effect of Ramadan fasting on markers of oxidative stress and serum biochemical markers of cellular damage in healthy subjects. Ann Nutr Metab. 2008;53(3–4):175–81. https://www.ncbi.nlm.nih.gov/pubmed/19011280. | Daily Eating Occasions Not Reported
437 | Ikeda N, Nishi N. First incidence and associated factors of overweight and obesity from preschool to primary school: longitudinal analysis of a national cohort in Japan. Int J Obes (Lond). 2019. 43:751–760 https://www.ncbi.nlm.nih.gov/pubmed/30659255 | Daily Eating Occasions Not Reported
438 | Influences of breakfast on clock gene and ampk mrna expression and postprandial glycemia in healthy and type 2 diabetes. Diabetes. 2017;66:A54 | Publication Status
439 | Ishimoto Y, Yoshida M, Nagata K, Yamada H, Hashizume H, Yoshimura N. Consuming breakfast and exercising longer during high school increases bone mineral density in young adult men. J Bone Miner Metab. 2013. 31:329–36 https://www.ncbi.nlm.nih.gov/pubmed/23263782 | Daily Eating Occasions Not Reported
440 | Iwasaki T, Hirose A, Azuma T, Ohashi T, Watanabe K, Obora A, Deguchi F, Kojima T, Isozaki A, Tomofuji T. Association between eating behavior and poor glycemic control in Japanese adults. Sci Rep. 2019. 9:3418 https://www.ncbi.nlm.nih.gov/pubmed/30833585 | Study Design, Eating Frequency Data Collection
441 | Jaaskelainen A, Schwab U, Kolehmainen M, Kaakinen M, Savolainen MJ, Froguel P, Cauchi S, Jarvelin MR, Laitinen J. Meal frequencies modify the effect of common genetic variants on body mass index in adolescents of the northern Finland birth cohort 1986. PLoS One. 2013. 8:e73802 https://www.ncbi.nlm.nih.gov/pubmed/24040077 | Study Design
442 | Jaaskelainen A, Schwab U, Kolehmainen M, Pirkola J, Jarvelin MR, Laitinen J. Associations of meal frequency and breakfast with obesity and metabolic syndrome traits in adolescents of Northern Finland Birth Cohort 1986. Nutr Metab Cardiovasc Dis. 2013. 23:1002–9 https://www.ncbi.nlm.nih.gov/pubmed/22901841 | Study Design
443 | Jakubowicz D, Barnea M, Wainstein J, Froy O. High caloric intake at breakfast vs. dinner differentially influences weight loss of overweight and obese women. Obesity (Silver Spring). 2013. 21:2504–12 https://www.ncbi.nlm.nih.gov/pubmed/23512957 | Intervention/Exposure, Comparator
444 | Jakubowicz D, Boaz M, Bar-Dayan Y, Wainstein J. Comparison of the effect of high calorie breakfast diet vs high calorie dinner diet on weight loss, ghrelin, lipids and appetite scores in obese non diabetic women. Endocrine reviews. 2012;33(12). | Study Design, Publication Status
445 | Jakubowicz D, Dayan YB, Wainstein J. The influence of meal timing on glucose metabolism and hyperandrogenism in lean women with polycystic ovary syndrome. Diabetes. 2013. 62:A399 | Health Status
446 | Jakubowicz D, Wainstein J, Froy O. High-calorie breakfast improves weight loss and metabolism vs. isocaloric meal at dinner in obese women with metabolic syndrome. Diabetes. 2013. 62:A399 | Publication Status
447 | Jakubowicz D, Wainstein J, Landau Z, Raz I, Ahren B, Chapnik N, Ganz T, Menaged M, Barnea M, Bar-Dayan Y, Publication Status etal. Influences of breakfast on circadian clock gene and AMPK mRNA expression and postprandial glycemia in healthy individuals and individuals with diabetes. Clinical obesity. 2018. 8:2–3 https://www.cochranelibrary.com/central/doi/10.1002/central/CN-01571505/full | Publication Status
448 | Jakubowicz D, Wainstein J, Landau Z, Raz I, Ahren B, Chapnik N, Ganz T, Menaged M, Barnea M, Bar-Dayan Y, Froy O. Influences of Breakfast on Clock Gene Expression and Postprandial Glycemia in Healthy Individuals and Individuals With Diabetes: A Randomized Clinical Trial. Diabetes Care. 2017. 40:1573–1579 https://www.ncbi.nlm.nih.gov/pubmed/28830875 | Daily Eating Occasions Not Reported
449 | Jamshed H, Beyl RA, Della Manna DL, Yang ES, Ravussin E, Peterson CM. Early Time-Restricted Feeding Improves 24-Hour Glucose Levels and Affects Markers of the Circadian Clock, Aging, and Autophagy in Humans. Nutrients. 2019;11(6). https://www.ncbi.nlm.nih.gov/pubmed/31151228. | Daily Eating Occasions Not Reported, Comparator, Size of Study Groups
450 | Jarrar AH, Beasley JM, Ohuma EO, Cheikh Ismail L, Qeshta DA, Mohamad MN, et al. Effect of High Fiber Cereal Intake on Satiety and Gastrointestinal Symptoms during Ramadan. Nutrients. 2019;11(4). https://www.ncbi.nlm.nih.gov/pubmed/31027300. | Intervention/Exposure, Comparator
451 | Jebeile H, Gow ML, Lister N, Chisholm K, Grunseit A, Alexander S, Haghighi MM, Ayer J, Cowell CT, Baur L, etal. Intermittent energy restriction in adolescents with obesity: a pilot study. Obesity facts. 2018. 11:218–219 | Publication Status
452 | Jebeile H, Gow ML, Lister NB, Mosalman Haghighi M, Ayer J, Cowell CT, Baur LA, Garnett SP. Intermittent Energy Restriction Is a Feasible, Effective, and Acceptable Intervention to Treat Adolescents with Obesity. J Nutr. 2019. 149:1189–1197 https://www.ncbi.nlm.nih.gov/pubmed/31006807 | Daily Eating Occasions Not Reported
453 | Jeffery RW, Abbott G, Ball K, Crawford D. Behavior and weight correlates of weight-control efforts in Australian women living in disadvantage: The READI study. International journal of behavioral nutrition and physical activity. 2013;10. https://www.ncbi.nlm.nih.gov/pubmed/23621952. | Intervention/Exposure, Daily Eating Occasions Not Reported
454 | Jennings M. Snacking ourselves sick. HDA Now. 2012:25. https://www.ncbi.nlm.nih.gov/pubmed/22988698. | Study Design, Intervention/Exposure, Publication Status
455 | Jensen MD, Ekberg K, Landau BR. Lipid metabolism during fasting. Am J Physiol Endocrinol Metab. 2001. 281:E789–93 https://www.ncbi.nlm.nih.gov/pubmed/11551856 | Intervention/Exposure, Size of Study Groups
456 | Jensen ML, Corvalan C, Reyes M, Popkin BM, Taillie LS. Snacking patterns among Chilean children and adolescents: is there potential for improvement? Public Health Nutr. 2019:1–10. https://www.ncbi.nlm.nih.gov/pubmed/31124768. | Study Design
457 | Jimenez AM, Oliva SL, Vilar EG, De Cuevillas B, Morais Moreno MDC, Gabella De Prado J, Diaz EA, Mauro Martin IS. The Mediterranean diet pattern with intermittent semi-fasting may facilitate weight loss: randomised controlled trial. Mediterranean journal of nutrition and metabolism. 2019. 12:153–161 | Daily Eating Occasions Not Reported
458 | Johnson JB, Laub DR, John S. The effect on health of alternate day calorie restriction: eating less and more than needed on alternate days prolongs life. Med Hypotheses. 2006. 67:209–11 https://www.ncbi.nlm.nih.gov/pubmed/16529878 | Study Design
459 | Johnson NA, Stannard SR, Rowlands DS, Chapman PG, Thompson CH, O’Connor H, Sachinwalla T, Thompson MW. Effect of short-term starvation versus high-fat diet on intramyocellular triglyceride accumulation and insulin resistance in physically fit men. Exp Physiol. 2006. 91:693–703 https://www.ncbi.nlm.nih.gov/pubmed/16627573 | Intervention/Exposure, Size of Study Groups
460 | Johnstone AM, Faber P, Gibney ER, Elia M, Horgan G, Golden BE, Stubbs RJ. Effect of an acute fast on energy compensation and feeding behaviour in lean men and women. Int J Obes Relat Metab Disord. 2002. 26:1623–8 https://www.ncbi.nlm.nih.gov/pubmed/12461679 | Intervention/Exposure, Daily Eating Occasions Not Reported
461 | Jong-Hyuck K, Wi-Young S. Association between Frequency of Breakfast Eating and Obesity in Korean Adolescents. Iranian Journal of Public Health. 2012;41(6):50–7. https://www.ncbi.nlm.nih.gov/pubmed/23113193. | Study Design
462 | Jurikova J, Julinkova S. Eating habits of students in Vyskov (The Czech Republic). Rocz Panstw Zakl Hig. 2007. 58:423–6 https://www.ncbi.nlm.nih.gov/pubmed/17929589 | Study Design
463 | Kachurak A, Davey A, Bailey RL, Fisher JO. Daily Snacking Occasions and Weight Status Among US Children Aged 1 to 5 Years. Obesity (Silver Spring). 2018. 26:1034–1042 https://www.ncbi.nlm.nih.gov/pubmed/29656571 | Study Design
464 | Kaczmarek JL, Musaad SM, Holscher HD. Time of day and eating behaviors are associated with the composition and function of the human gastrointestinal microbiota. Am J Clin Nutr. 2017. 106:1220–1231 https://www.ncbi.nlm.nih.gov/pubmed/28971851 | Outcome
465 | Kahleova H, Lloren JI, Mashchak A, Hill M, Fraser GE. Meal Frequency and Timing Are Associated with Changes in Body Mass Index in Adventist Health Study 2. J Nutr. 2017. 147:1722–1728 https://www.ncbi.nlm.nih.gov/pubmed/28701389 | Study Design
466 | Kajiyama S, Imai S, Hashimoto Y, Yamane C, Miyawaki T, Matsumoto S, Ozasa N, Tanaka M, Kajiyama S, Fukui M. Divided consumption of late-night-dinner improves glucose excursions in young healthy women: A randomized cross-over clinical trial. Diabetes Res Clin Pract. 2018. 136:78–84 https://www.ncbi.nlm.nih.gov/pubmed/29199002 | Comparator
467 | Kakamu T, Hidaka T, Kumagai T, Masuishi Y, Kasuga H, Endo S, Sato S, Takeda A, Koizumi M, Fukushima T. Unhealthy changes in eating habits cause acute onset hypertension in the normotensive community-dwelling elderly-3 years cohort study. Medicine (Baltimore). 2019. 98:e15071 https://www.ncbi.nlm.nih.gov/pubmed/30985658 | Daily Eating Occasions Not Reported
468 | Kalam F, Kroeger CM, Trepanowski JF, Gabel K, Song JH, Cienfuegos S, Varady KA. Beverage intake during alternate-day fasting: Relationship to energy intake and body weight. Nutr Health. 2019. 25:167–171 https://www.ncbi.nlm.nih.gov/pubmed/30983506 | Intervention/Exposure
469 | Kanaley JA, Heden TD, Liu Y, Fairchild TJ. Alteration of postprandial glucose and insulin concentrations with meal frequency and composition. Br J Nutr. 2014. 112:1484–93 https://www.ncbi.nlm.nih.gov/pubmed/25231499 | Size of Study Groups
470 | Kaneita Y, Uchiyama M, Yoshiike N, Ohida T. Associations of usual sleep duration with serum lipid and lipoprotein levels. Sleep. 2008;31(5):645–52. https://www.ncbi.nlm.nih.gov/pubmed/18517035 | Study Design
471 | Kaneta T, Hakamatsuka T, Takanami K, Yamada T, Takase K, Sato A, Higano S, Kinomura S, Fukuda H, Takahashi S, Yamada S. Evaluation of the relationship between physiological FDG uptake in the heart and age, blood glucose level, fasting period, and hospitalization. Ann Nucl Med. 2006. 20:203–8 https://www.ncbi.nlm.nih.gov/pubmed/16715951 | Intervention/Exposure
472 | Kanyamee Mayurachat, Fongkaew Warunee, Chotibang Jutamas, Aree Patcharaporn, Christine Kennedy. An Intervention Study of Changing Eating Behaviors and Reducing Weight in Thai Children Aged 10-12. Pacific Rim International Journal of Nursing Research. 2013. 17:317–328 | Intervention/Exposure
473 | Karateke A, Kaplanoglu M, Avci F, Kurt RK, Baloglu A. The effect of ramadan fasting on fetal development. Pakistan journal of medical sciences. 2015;31(6):1295–9. https://www.ncbi.nlm.nih.gov/pubmed/26870085. | Daily Eating Occasions Not Reported, Outcome
474 | Karfopoulou E, Brikou D, Mamalaki E, Bersimis F, Anastasiou CA, Hill JO, Yannakoulia M. Dietary patterns in weight loss maintenance: results from the MedWeight study. Eur J Nutr. 2017. 56:991–1002 https://www.ncbi.nlm.nih.gov/pubmed/26744302 | Intervention/Exposure
475 | Karkkainen U, Mustelin L, Raevuori A, Kaprio J, Keski-Rahkonen A. Successful weight maintainers among young adults-A ten-year prospective population study. Eat Behav. 2018. 29:91–98 https://www.ncbi.nlm.nih.gov/pubmed/29549864 | Daily Eating Occasions Not Reported
476 | Karwacki-Marugg C, Huddy K, Bernstein B, Whitaker M, Pranitis L, Morse B, Colangelo R, Stuart M, ODonnell M, Kelsey AM. Support for Women Achieving Cardiovascular Health Through Exercise And Nutrition (SWAN) Study Pilot. Conn Med. 2016. 80:69–74 https://www.ncbi.nlm.nih.gov/pubmed/27024976 | Intervention/Exposure
477 | Kassab S, Abdul-Ghaffar T, Nagalla DS, Sachdeva U, Nayar U. Interactions between leptin, neuropeptide-Y and insulin with chronic diurnal fasting during Ramadan. Ann Saudi Med. 2004. 24:345–9 https://www.ncbi.nlm.nih.gov/pubmed/15573845 | Daily Eating Occasions Not Reported
478 | Kassab SE, Abdul-Ghaffar T, Nagalla DS, Sachdeva U, Nayar U. Serum leptin and insulin levels during chronic diurnal fasting. Asia Pac J Clin Nutr. 2003. 12:483–7 https://www.ncbi.nlm.nih.gov/pubmed/14672875 | Intervention/Exposure, Daily Eating Occasions Not Reported
479 | Kaufman FR, Hirst K, Linder B, Baranowski T, Cooper DM, Foster GD, Goldberg L, Harrell JS, Marcus MD, Trevino RP. Risk factors for type 2 diabetes in a sixth- grade multiracial cohort: the HEALTHY study. Diabetes Care. 2009. 32:953–5 https://www.ncbi.nlm.nih.gov/pubmed/19196888 | Study Design
480 | Kavehmanesh Z, Abolghasemi H. Maternal Ramadan fasting and neonatal health. J Perinatol. 2004. 24:748–50 https://www.ncbi.nlm.nih.gov/pubmed/15343350 | Intervention/Exposure, Daily Eating Occasions Not Reported, Country
481 | Kent LM, Worsley A. Breakfast size is related to body mass index for men, but not women. Nutr Res. 2010. 30:240–5 https://www.ncbi.nlm.nih.gov/pubmed/20534326 | Study Design
482 | Keogh JB, Pedersen E, Petersen KS, Clifton PM. Effects of intermittent compared to continuous energy restriction on short-term weight loss and long-term weight loss maintenance. Clin Obes. 2014. 4:150–6 https://www.ncbi.nlm.nih.gov/pubmed/25826770 | Intervention/Exposure, Daily Eating Occasions Not Reported
483 | Kerr MA, Rennie KL, McCaffrey TA, Wallace JM, Hannon-Fletcher MP, Livingstone MB. Snacking patterns among adolescents: a comparison of type, frequency and portion size between Britain in 1997 and Northern Ireland in 2005. Br J Nutr. 2009. 101:122–31 https://www.ncbi.nlm.nih.gov/pubmed/18533071 | Study Design, Outcome
484 | Keski-Rahkonen A, Bulik CM, Pietilainen KH, Rose RJ, Kaprio J, Rissanen A. Eating styles, overweight and obesity in young adult twins. Eur J Clin Nutr. 2007. 61:822–9 https://www.ncbi.nlm.nih.gov/pubmed/17251930 | Daily Eating Occasions Not Reported
485 | Keski-Rahkonen A, Kaprio J, Rissanen A, Virkkunen M, Rose RJ. Breakfast skipping and health-compromising behaviors in adolescents and adults. Eur J Clin Nutr. 2003. 57:842–53 https://www.ncbi.nlm.nih.gov/pubmed/12821884 | Study Design
486 | Kessler CS, Stange R, Schlenkermann M, Jeitler M, Michalsen A, Selle A, Raucci F, Steckhan N. A nonrandomized controlled clinical pilot trial on 8 wk of intermittent fasting (24 h/wk). Nutrition. 2018. 46:143–152.e2 https://www.ncbi.nlm.nih.gov/pubmed/29031771 | Daily Eating Occasions Not Reported, Size of Study Groups
487 | Khan N, Rasheed A, Ahmed H, Aslam F, Kanwal F. Effect of Ramadan fasting on glucose level, lipid profile, HbA1c and uric acid among medical students in Karachi, Pakistan. East Mediterr Health J. 2017. 23:274–279 https://www.ncbi.nlm.nih.gov/pubmed/28634977 | Daily Eating Occasions Not Reported, Country
488 | Khochtali I, Hellara I, Chakroun T, Harzallah O, Dridi Z, Hamdi S, Hassine M, Nouira S. Effects of long term intermittent fasting on biochemical and homeostasis parameters (Ramadan research group prospective study). Diabetes. 2013. 62:A194 | Study Design, Publication Status
489 | Khoshdel A, Kheiri S, Hashemi-Dehkordi E, Nasiri J, Shabanian-Borujeni S, Saedi E. The effect of Ramadan fasting on LH, FSH, oestrogen, progesterone and leptin in pregnant women. J Obstet Gynaecol. 2014. 34:634–8 https://www.ncbi.nlm.nih.gov/pubmed/24914688 | Intervention/Exposure, Daily Eating Occasions Not Reported
490 | Khoshdel A, Kheiri S, Nasiri J, Taheri E, Najafi M, Salehifard AZ, Jafari A. Comparison of growth parameters of infants of Ramadan fasted and non-fasted mothers. Iranian Journal of Endocrinology & Metabolism. 2008. 10:188–188 | Study Design, Daily Eating Occasions Not Reported, Outcome
491 | Kim J, Kang SW, Mallilankaraman K, Baik SH, Lim JC, Balaganapathy P, She DT, Lok KZ, Fann DY, Thambiayah U, Tang SC, Stranahan AM, Dheen ST, Gelderblom M, Seet RC, Karamyan VT, Vemuganti R, Sobey CG, Mattson MP, Jo DG, Arumugam TV. Transcriptome analysis reveals intermittent fasting-induced genetic changes in ischemic stroke. Hum Mol Genet. 2018. 27:2405 https://www.ncbi.nlm.nih.gov/pubmed/29688516 | Publication Status
492 | Kim KW, Song MY, Chung SH, Chung WS. Effect of modified fasting therapy on body weight, fat and muscle mass, and blood chemistry in patients with obesity. J Tradit Chin Med. 2016. 36:57–62 https://www.ncbi.nlm.nih.gov/pubmed/26946620 | Study Design, Intervention/Exposure, Daily Eating Occasions Not Reported
493 | Kim S, DeRoo LA, Sandler DP. Eating patterns and nutritional characteristics associated with sleep duration. Public Health Nutr. 2011. 14:889–95 https://www.ncbi.nlm.nih.gov/pubmed/21029511 | Outcome
494 | King N, Wood R, Hills A, Byrne N, Salsibury-Salis A. Responses in appetite and eating behaviour to 16 weeks of energy restriction in obese males. Obesity facts. 2012. 5:34–35 | Publication Status
495 | Kirkendall DT, Leiper JB, Bartagi Z, Dvorak J, Zerguini Y. The influence of Ramadan on physical performance measures in young Muslim footballers. Journal of sports sciences. 2008;26:S15–27. https://www.ncbi.nlm.nih.gov/pubmed/19085449. | Daily Eating Occasions Not Reported, Outcome
496 | Kishel GF. Obesity in children. Minn Med. 2003. 86:18–9 https://www.ncbi.nlm.nih.gov/pubmed/14658553 | Study Design
497 | Kito K, Kuriyama A, Takahashi Y, Nakayama T. Impacts of skipping breakfast and late dinner on the incidence of being overweight: a 3-year retrospective cohort study of men aged 20-49 years. J Hum Nutr Diet. 2019. 32:349–355 https://www.ncbi.nlm.nih.gov/pubmed/30821869 | Daily Eating Occasions Not Reported, Eating Frequency Data Collection
498 | Kiyak Caglayan E, Engin-Ustun Y, Sari N, Gocmen AY, Polat MF. The effects of prolonged fasting on the levels of adiponectin, leptin, apelin, and omentin in pregnant women. J Obstet Gynaecol. 2016. 36:555–8 https://www.ncbi.nlm.nih.gov/pubmed/26759187 | Daily Eating Occasions Not Reported
499 | Kiyani MM, Memon AR, Amjad MI, Ameer MR, Sadiq M, Mahmood T. Study of Human Biochemical Parameters During and After Ramadan. J Relig Health. 2017. 56:55–62 https://www.ncbi.nlm.nih.gov/pubmed/26149778 | Country
500 | Kiziltan G, Karabudak E, Tuncay G, Avsar F, Tuncay P, Mungan O, Meral P. Dietary intake and nutritional status of Turkish pregnant women during Ramadan. Saudi Med J. 2005. 26:1782–7 https://www.ncbi.nlm.nih.gov/pubmed/16311666 | Country
501 | Klempel MC, Bhutani S, Fitzgibbon M, Freels S, Varady KA. Dietary and physical activity adaptations to alternate day modified fasting: implications for optimal weight loss. Nutr J. 2010. 9:35 https://www.ncbi.nlm.nih.gov/pubmed/20815899 | Daily Eating Occasions Not Reported
502 | Klempel MC, Kroeger CM, Bhutani S, Trepanowski JF, Varady KA. Intermittent fasting combined with calorie restriction is effective for weight loss and cardio-protection in obese women. Nutr J. 2012. 11:98 https://www.ncbi.nlm.nih.gov/pubmed/23171320 | Daily Eating Occasions Not Reported, Comparator
503 | Klempel MC, Kroeger CM, Norkeviciute E, Goslawski M, Phillips SA, Varady KA. Benefit of a low-fat over high-fat diet on vascular health during alternate day fasting. Nutr Diabetes. 2013. 3:e71 https://www.ncbi.nlm.nih.gov/pubmed/23712283 | Daily Eating Occasions Not Reported, Comparator
504 | Klempel MC, Kroeger CM, Varady KA. Alternate day fasting (ADF) with a high fat background diet produces similar weight loss and cardio-protection when compared to ADF with a low fat background diet. FASEB journal. 2012;26. | Study Design, Publication Status
505 | Klempel MC, Kroeger CM, Varady KA. Alternate day fasting (ADF) with a high-fat diet produces similar weight loss and cardio-protection as ADF with a low-fat diet. Metabolism. 2013. 62:137–43 https://www.ncbi.nlm.nih.gov/pubmed/22889512 | Intervention/Exposure, Comparator
506 | Klempel MC, Kroeger CM, Varady KA. Alternate day fasting increases LDL particle size independently of dietary fat content in obese humans. Eur J Clin Nutr. 2013. 67:783–5 https://www.ncbi.nlm.nih.gov/pubmed/23612508 | Intervention/Exposure, Daily Eating Occasions Not Reported
507 | Klingenberg L, Chaput JP, Holmbck U, Jennum P, Astrup A, Sjdin A. Sleep restriction is not associated with a positive energy balance in adolescent boys. American Journal of Clinical Nutrition. 2012. 96:240–248 | Intervention/Exposure, Daily Eating Occasions Not Reported
508 | Knutsson A, Karlsson B, Ornkloo K, Landstrom U, Lennernas M, Eriksson K. Postprandial responses of glucose, insulin and triglycerides: influence of the timing of meal intake during night work. Nutr Health. 2002. 16:133–41 https://www.ncbi.nlm.nih.gov/pubmed/12102366 | Study Design, Comparator
509 | Ko GT, Chan JC, Tong SD, Chan AW, Wong PT, Hui SS, Kwok R, Chan CL. Associations between dietary habits and risk factors for cardiovascular diseases in a Hong Kong Chinese working populationthe Better Health for Better Hong Kong (BHBHK) health promotion campaign. Asia Pac J Clin Nutr. 2007. 16:757–65 https://www.ncbi.nlm.nih.gov/pubmed/18042539 | Study Design, Intervention/Exposure, Daily Eating Occasions Not Reported
510 | Kobayashi F, Ogata H, Omi N, Nagasaka S, Yamaguchi S, Hibi M, Tokuyama K. Effect of breakfast skipping on diurnal variation of energy metabolism and blood glucose. Obes Res Clin Pract. 2014. 8:e201–98 https://www.ncbi.nlm.nih.gov/pubmed/24847666 | Comparator, Size of Study Groups
511 | Kobel S, Wirt T, Schreiber A, Kesztys D, Kettner S, Erkelenz N, Wartha O, Steinacker JM. Intervention effects of a school-based health promotion programme on obesity related behavioural outcomes. Journal of obesity. 2014. 2014:476230 | Daily Eating Occasions Not Reported
512 | Kolbert E. XXXL: why are we so fat? New Yorker. 2009:73–7. https://www.ncbi.nlm.nih.gov/pubmed/19697500. | Publication Status
513 | Kolettis TM, Papathanasiou A, Tziallas D, Milionis HJ, Kastanioti CK, Achenbach K. Afternoon nap, meal ingestion and circadian variation of acute myocardial infarction. International journal of cardiology. 2008;123(3):338–40. https://www.ncbi.nlm.nih.gov/pubmed/17320206. | Study Design
514 | Kong A, Beresford SA, Alfano CM, Foster-Schubert KE, Neuhouser ML, Johnson DB, Duggan C, Wang CY, Xiao L, Bain CE, McTiernan A. Associations between snacking and weight loss and nutrient intake among postmenopausal overweight to obese women in a dietary weight-loss intervention. J Am Diet Assoc. 2011. 111:1898–903 https://www.ncbi.nlm.nih.gov/pubmed/22117666 | Study Design, Daily Eating Occasions Not Reported
515 | Kong A, Beresford SAA, Alfano CM, Foster-Schubert KE, Neuhouser ML, Johnson DB, Duggan C, Wang CY, Xiao L, Jeffery RW, Bain CE, McTiernan A. Self-monitoring and eating-related behaviors are associated with 12-month weight loss in postmenopausal overweight-to-obese women. J Acad Nutr Diet. 2012. 112:1428–1435 https://www.ncbi.nlm.nih.gov/pubmed/22795495 | Intervention/Exposure, Daily Eating Occasions Not Reported
516 | Koopman KE, Caan MW, Nederveen AJ, Pels A, Ackermans MT, Fliers E, la Fleur SE, Serlie MJ. Hypercaloric diets with increased meal frequency, but not meal size, increase intrahepatic triglycerides: a randomized controlled trial. Hepatology. 2014. 60:545–53 https://www.ncbi.nlm.nih.gov/pubmed/24668862 | Intervention/Exposure
517 | Kordi R, Abdollahi M, Memari A-H, Najafabadi MG. Investigating Two Different Training Time Frames during Ramadan Fasting. Asian Journal of Sports Medicine. 2011;2(3):205–10. https://www.ncbi.nlm.nih.gov/pubmed/22375240. | Daily Eating Occasions Not Reported
518 | Kostecka M. The influence of preschool childrens diets on the risk of lifestyle diseases. A pilot study. Rocz Panstw Zakl Hig. 2018. 69:139–145 https://www.ncbi.nlm.nih.gov/pubmed/29766692 | Study Design
519 | Kosti RI, Panagiotakos DB, Mihas CC, Alevizos A, Zampelas A, Mariolis A, Tountas Y. Dietary habits, physical activity and prevalence of overweight/obesity among adolescents in Greece: the Vyronas study. Med Sci Monit. 2007. 13:Cr437–44 https://www.ncbi.nlm.nih.gov/pubmed/17901850 | Study Design
520 | Kovtun K. Meal and sleep timing interact to affect total caloric intake. Sleep. 2016. 39:A55–A56 | Publication Status
521 | Kral TV, Whiteford LM, Heo M, Faith MS. Effects of eating breakfast compared with skipping breakfast on ratings of appetite and intake at subsequent meals in 8- to 10-y-old children. Am J Clin Nutr. 2011. 93:284–91 https://www.ncbi.nlm.nih.gov/pubmed/21084650 | Daily Eating Occasions Not Reported, Outcome
522 | Kral TVE, Chittams J, Moore RH. Relationship between food insecurity, child weight status, and parent-reported child eating and snacking behaviors. J Spec Pediatr Nurs. 2017;22(2). https://www.ncbi.nlm.nih.gov/pubmed/28321980. | Study Design
523 | Kroeger C, Trapanowski J, Barnosky A, Klempel M, Varady K. Effect of 1 year of alternate day fasting versus daily calorie restriction on type 2 diabetes risk. FASEB journal. 2015;29 | Study Design, Publication Status
524 | Kroeger C, Trapanowski J, Klempel M, Bhutani S, Hoddy K, Varady K. Alternate day fasting is effective for weight loss and weight maintenance in obese adults. FASEB journal. 2014;28S1 | Study Design, Publication Status
525 | Kroeger CM, Klempel MC, Bhutani S, Trepanowski JF, Tangney CC, Varady KA. Improvement in coronary heart disease risk factors during an intermittent fasting/calorie restriction regimen: Relationship to adipokine modulations. Nutr Metab (Lond). 2012. 9:98 https://www.ncbi.nlm.nih.gov/pubmed/23113919 | Study Design, Daily Eating Occasions Not Reported
526 | Kroeger CM, Klempel MC, Bhutani S, Trepanowski JF, Varady KA. Improvement in coronary heart disease risk factors during an intermittent fasting/calorie restriction regimen: relationship to adipokine modulations. FASEB journal. 2013. 27(12). | Study Design, Publication Status
527 | Kroeger CM, Trepanowski JF, Klempel MC, Barnosky A, Bhutani S, Gabel K, Varady KA. Eating behavior traits of successful weight losers during 12 months of alternate-day fasting: An exploratory analysis of a randomized controlled trial. Nutr Health. 2018. 24:5–10 https://www.ncbi.nlm.nih.gov/pubmed/29353535 | Intervention/Exposure, Daily Eating Occasions Not Reported
528 | Kubota Y, Iso H, Sawada N, Tsugane S. Association of Breakfast Intake With Incident Stroke and Coronary Heart Disease: The Japan Public Health Center-Based Study. Stroke. 2016. 47:477–81 https://www.ncbi.nlm.nih.gov/pubmed/26732562 | Daily Eating Occasions Not Reported
529 | Kudo A, Asahi K, Satoh H, Iseki K, Moriyama T, Yamagata K, Tsuruya K, Fujimoto S, Narita I, Konta T, Kondo M, Shibagaki Y, Kasahara M, Watanabe T, Shimabukuro M. Fast eating is a strong risk factor for new-onset diabetes among the Japanese general population. Sci Rep. 2019. 9:8210 https://www.ncbi.nlm.nih.gov/pubmed/31160664 | Daily Eating Occasions Not Reported, Eating Frequency Data Collection
530 | Kullen C, Prvan T, OConnor H. Barriers and Enablers Influencing Dietary Practices in Australian Army Personnel. Mil Med. 2019. 184:e213–e221 https://www.ncbi.nlm.nih.gov/pubmed/30371876 | Study Design
531 | Kupers LK, de Pijper JJ, Sauer PJ, Stolk RP, Corpeleijn E. Skipping breakfast and overweight in 2- and 5-year-old Dutch children-the GECKO Drenthe cohort. Int J Obes (Lond). 2014. 38:569–71 https://www.ncbi.nlm.nih.gov/pubmed/24158122 | Study Design
532 | Lam BCC, Han JSY, Ho CY, Teoh H, Yum MPS, Wong MTK, Koh GCH. The effect of intermittent energy restriction using meal replacements in overweight chinese subjects: a pilot randomized control trial. Obesity facts. 2018. 11:307 | Publication Status
533 | Lamine F, Bouguerra R, Jabrane J, Marrakchi Z, Ben Rayana MC, Ben Slama C, Gaigi S. Food intake and high density lipoprotein cholesterol levels changes during ramadan fasting in healthy young subjects. Tunis Med. 2006. 84:647–50 https://www.ncbi.nlm.nih.gov/pubmed/17193859 | Daily Eating Occasions Not Reported
534 | Lamri-Senhadji MY, El Kebir B, Belleville J, Bouchenak M. Assessment of dietary consumption and time-course of changes in serum lipids and lipoproteins before, during and after Ramadan in young Algerian adults. Singapore Med J. 2009. 50:288–94 https://www.ncbi.nlm.nih.gov/pubmed/19352573 | Intervention/Exposure, Daily Eating Occasions Not Reported
535 | Langlet B, Tang Bach M, Odegi D, Fagerberg P, Ioakimidis I. The Effect of Food Unit Sizes and Meal Serving Occasions on Eating Behaviour Characteristics: Within Person Randomised Crossover Studies on Healthy Women. Nutrients. 2018;10(7). https://www.ncbi.nlm.nih.gov/pubmed/29986529. | Intervention/Exposure, Daily Eating Occasions Not Reported
536 | Laraia BA, Adler NE, Coleman-Phox K, Vieten C, Mellin L, Kristeller JL, Thomas M, Stotland NE, Lustig RH, Dallman MF, Hecht FM, Bush NR, de Groat CL, Epel E. Novel Interventions to Reduce Stress and Overeating in Overweight Pregnant Women: A Feasibility Study. Matern Child Health J. 2018. 22:670–678 https://www.ncbi.nlm.nih.gov/pubmed/29455384 | Intervention/Exposure, Outcome, Size of Study Groups
537 | Larsen SC, Heitmann BL. More Frequent Intake of Regular Meals and Less Frequent Snacking Are Weakly Associated with Lower Long-Term Gains in Body Mass Index and Fat Mass in Middle-Aged Men and Women. J Nutr. 2019. 149:824–830 https://www.ncbi.nlm.nih.gov/pubmed/31034009 | Eating Frequency Data Collection
538 | Larson N, Chen Y, Wall M, Winkler MR, Goldschmidt AB, Neumark-Sztainer D. Personal, behavioral, and environmental predictors of healthy weight maintenance during the transition to adulthood. Prev Med. 2018. 113:80–90 https://www.ncbi.nlm.nih.gov/pubmed/29727637 | Intervention/Exposure, Daily Eating Occasions Not Reported
539 | Larson NI, Neumark-Sztainer D, Story M. Weight control behaviors and dietary intake among adolescents and young adults: longitudinal findings from Project EAT. J Am Diet Assoc. 2009. 109:1869–77 https://www.ncbi.nlm.nih.gov/pubmed/19857628 | Outcome
540 | Larsson I, Hulthen L, Landen M, Palsson E, Janson P, Stener-Victorin E. Dietary intake, resting energy expenditure, and eating behavior in women with and without polycystic ovary syndrome. Clin Nutr. 2016. 35:213–8 https://www.ncbi.nlm.nih.gov/pubmed/25743212 | Study Design
541 | Laska MN, Lytle LA, Nanney MS, Moe SG, Linde JA, Hannan PJ. Results of a 2-year randomized, controlled obesity prevention trial: Effects on diet, activity and sleep behaviors in an at-risk young adult population. Prev Med. 2016. 89:230–236 https://www.ncbi.nlm.nih.gov/pubmed/27283096 | Daily Eating Occasions Not Reported
542 | Laska MN, Murray DM, Lytle LA, Harnack LJ. Longitudinal associations between key dietary behaviors and weight gain over time: transitions through the adolescent years. Obesity (Silver Spring). 2012. 20:118–25 https://www.ncbi.nlm.nih.gov/pubmed/21701567 | Daily Eating Occasions Not Reported
543 | Latiri I, Sandid S, Fennani MA, Hadrich M, Masmoudi T, Maatoug C, Zammit-Chatti M, Chamari K, Ben Saad H. The Effects of Ramadan Fasting on the Spirometric Data of Healthy Adult Males. Am J Mens Health. 2017. 11:1214–1223 https://www.ncbi.nlm.nih.gov/pubmed/28625120 | Daily Eating Occasions Not Reported, Outcome
544 | Lavizzo-Mourey R. The adolescent obesity epidemic. J Adolesc Health. 2009. 45:S6–7 https://www.ncbi.nlm.nih.gov/pubmed/19699438 | Study Design
545 | Laxer RE, Brownson RC, Dubin JA, Cooke M, Chaurasia A, Leatherdale ST. Clustering of risk-related modifiable behaviours and their association with overweight and obesity among a large sample of youth in the COMPASS study. BMC Public Health. 2017. 17:102 https://www.ncbi.nlm.nih.gov/pubmed/28109270 | Study Design
546 | Lazzeri G, Giallombardo D, Guidoni C, Zani A, Casorelli A, Grasso A, Pozzi T, Rossi S, Giacchi M. Nutritional surveillance in Tuscany: eating habits at breakfast, mid-morning and afternoon snacks among 8-9 y-old children. J Prev Med Hyg. 2006. 47:91–9 https://www.ncbi.nlm.nih.gov/pubmed/17217185 | Study Design
547 | Leahy K, Berlin KS, Banks GG, Bachman J. The Relationship Between Intuitive Eating and Postpartum Weight Loss. Matern Child Health J. 2017. 21:1591–1597 https://www.ncbi.nlm.nih.gov/pubmed/28176035 | Study Design, Intervention/Exposure
548 | Leblanc V, Provencher V, Begin C, Corneau L, Tremblay A, Lemieux S. Long-term effects of a Health-at-every-size intervention on eating patterns in premenopausal overweight women. FASEB journal. 2011;25. | Publication Status
549 | LeCheminant GM, LeCheminant JD, Tucker LA, Bailey BW. A randomized controlled trial to study the effects of breakfast on energy intake, physical activity, and body fat in women who are nonhabitual breakfast eaters. Appetite. 2017. 112:44–51 https://www.ncbi.nlm.nih.gov/pubmed/28063876 | Daily Eating Occasions Not Reported
550 | LeCheminant JD, Christenson E, Bailey BW, Tucker LA. Restricting night-time eating reduces daily energy intake in healthy young men: a short-term cross-over study. Br J Nutr. 2013. 110:2108–13 https://www.ncbi.nlm.nih.gov/pubmed/23702187 | Intervention/Exposure, Daily Eating Occasions Not Reported
551 | LeCroy MN, Truesdale KP, Matheson DM, Karp SM, Moore SM, Robinson TN, et al. Snacking characteristics and patterns and their associations with diet quality and BMI in the Childhood Obesity Prevention and Treatment Research Consortium. Public Health Nutr. 2019:1–11. https://www.ncbi.nlm.nih.gov/pubmed/31112114. | Study Design, Daily Eating Occasions Not Reported
552 | Lee EY, Kang B, Yang Y, Yang HK, Kim HS, Lim SY, Lee JH, Lee SS, Suh BK, Yoon KH. Study Time after School and Habitual Eating Are Associated with Risk for Obesity among Overweight Korean Children: A Prospective Study. Obes Facts. 2018. 11:46–55 https://www.ncbi.nlm.nih.gov/pubmed/29408816 | Daily Eating Occasions Not Reported, Eating Frequency Data Collection
553 | Lee SK. Acculturation, meal frequency, eating-out, and body weight in Korean Americans. Nutr Res Pract. 2008. 2:269–74 https://www.ncbi.nlm.nih.gov/pubmed/20016729 | Study Design
554 | Lee TS, Kim JS, Hwang YJ, Park YC. Habit of Eating Breakfast Is Associated with a Lower Risk of Hypertension. J Lifestyle Med. 2016. 6:64–67 https://www.ncbi.nlm.nih.gov/pubmed/27924285 | Study Design
555 | Leech RM, Timperio A, Worsley A, McNaughton SA. Eating patterns of Australian adults: associations with blood pressure and hypertension prevalence. Eur J Nutr. 2019. 58:1899–1909 https://www.ncbi.nlm.nih.gov/pubmed/29876653 | Study Design
556 | Leech RM, Worsley A, Timperio A, McNaughton SA. The role of energy intake and energy misreporting in the associations between eating patterns and adiposity. Eur J Clin Nutr. 2018. 72:142–147 https://www.ncbi.nlm.nih.gov/pubmed/28561038 | Study Design
557 | Leidy HJ, Armstrong CL, Tang M, Mattes RD, Campbell WW. The influence of higher protein intake and greater eating frequency on appetite control in overweight and obese men. Obesity (Silver Spring). 2010. 18:1725–32 https://www.ncbi.nlm.nih.gov/pubmed/20339363 | Eating Frequency Data Collection
558 | Leidy HJ, Hoertel HA, Douglas SM, Higgins KA, Shafer RS. A high-protein breakfast prevents body fat gain, through reductions in daily intake and hunger, in Breakfast skipping adolescents. Obesity (Silver Spring). 2015. 23:1761–4 https://www.ncbi.nlm.nih.gov/pubmed/26239831 | Daily Eating Occasions Not Reported, Comparator
559 | Leidy HJ, Hoertel HA, Douglas SM, Shafer RS. Daily addition of a protein-rich breakfast for long-term improvements in energy intake regulation and body weight management in overweight & obese ‘breakfast skipping’ young people. FASEB journal. 2013;27. | Study Design, Publication Status
560 | Leidy HJ, Racki EM. The addition of a protein-rich breakfast and its effects on acute appetite control and food intake in breakfast-skipping adolescents. Int J Obes (Lond). 2010. 34:1125–33 https://www.ncbi.nlm.nih.gov/pubmed/20125103 | Daily Eating Occasions Not Reported, Outcome
561 | Leidy HJ, Tang M, Armstrong CL, Martin CB, Campbell WW. The effects of consuming frequent, higher protein meals on appetite and satiety during weight loss in overweight/obese men. Obesity (Silver Spring). 2011. 19:818–24 https://www.ncbi.nlm.nih.gov/pubmed/20847729 | Outcome, Size of Study Groups
562 | Leiper JB, Maughan RJ, Kirkendall DT, Bartagi Z, Zerguini Y, Junge A, et al. The F-MARC study on Ramadan and football: research design, population, and environmental conditions. J Sports Sci. 2008;26 Suppl 3:S7–13. https://www.ncbi.nlm.nih.gov/pubmed/19085448. | Study Design, Publication Status
563 | Leiper JB, Watson P, Evans G, Dvorak J. Intensity of a training session during Ramadan in fasting and non-fasting Tunisian youth football players. Journal of Sports Sciences. 2008. 26:S71–9. https://www.ncbi.nlm.nih.gov/pubmed/19085454 | Daily Eating Occasions Not Reported
564 | Lemmens SG, Martens EA, Born JM, Martens MJ, Westerterp-Plantenga MS. Staggered meal consumption facilitates appetite control without affecting postprandial energy intake. J Nutr. 2011. 141:482–8 https://www.ncbi.nlm.nih.gov/pubmed/21270370 | Daily Eating Occasions Not Reported, Outcome
565 | Leong SL, Gray A, Haszard J, Horwath C. Weight-Control Methods, 3-Year Weight Change, and Eating Behaviors: A Prospective Nationwide Study of Middle-Aged New Zealand Women. J Acad Nutr Diet. 2016. 116:1276–84 https://www.ncbi.nlm.nih.gov/pubmed/27061782 | Intervention/Exposure
566 | Lessan N, Saadane I, Alkaf B, Hambly C, Buckley AJ, Finer N, Speakman JR, Barakat MT. The effects of Ramadan fasting on activity and energy expenditure. Am J Clin Nutr. 2018. 107:54–61 https://www.ncbi.nlm.nih.gov/pubmed/29381798 | Daily Eating Occasions Not Reported
567 | Lesser LI, Cohen DA, Brook RH. Changing eating habits for the medical profession. Jama. 2012. 308:983–4 https://www.ncbi.nlm.nih.gov/pubmed/22968886 | Publication Status
568 | Leuck M, Levandovski R, Harb A, Quiles C, Hidalgo MP. Circadian rhythm of energy expenditure and oxygen consumption. Journal of Parenteral and Enteral Nutrition. 2014;38(2):263–8. https://www.ncbi.nlm.nih.gov/pubmed/23599248. | Intervention/Exposure
569 | Leung GKW, Huggins CE, Bonham MP. Effect of meal timing on postprandial glucose responses to a low glycemic index meal: A crossover trial in healthy volunteers. Clin Nutr. 2019. 38:465–471 https://www.ncbi.nlm.nih.gov/pubmed/29248250 | Daily Eating Occasions Not Reported, Size of Study Groups
570 | Levitsky DA, Halbmaier CA, Mrdjenovic G. The freshman weight gain: a model for the study of the epidemic of obesity. Int J Obes Relat Metab Disord. 2004. 28:1435–42 https://www.ncbi.nlm.nih.gov/pubmed/15365585 | Daily Eating Occasions Not Reported
571 | Levitsky DA, Raea Limb JE, Wilkinson L, Sewall A, Zhong Y, Olabi A, Hunter J. Lack of negative autocorrelations of daily food intake on successive days challenges the concept of the regulation of body weight in humans. Appetite. 2017. 116:277–283 https://www.ncbi.nlm.nih.gov/pubmed/28483583 | Intervention/Exposure, Daily Eating Occasions Not Reported
572 | Li C, Ostermann T, Hardt M, Ludtke R, Broecker-Preuss M, Dobos G, Michalsen A. Metabolic and psychological response to 7-day fasting in obese patients with and without metabolic syndrome. Forsch Komplementmed. 2013. 20:413–20 https://www.ncbi.nlm.nih.gov/pubmed/24434755 | Intervention/Exposure, Daily Eating Occasions Not Reported
573 | Li G, Xie C, Lu S, Nichols RG, Tian Y, Li L, Patel D, Ma Y, Brocker CN, Yan T, Krausz KW, Xiang R, Gavrilova O, Patterson AD, Gonzalez FJ. Intermittent Fasting Promotes White Adipose Browning and Decreases Obesity by Shaping the Gut Microbiota. Cell Metab. 2017. 26:801 https://www.ncbi.nlm.nih.gov/pubmed/29117546 | Study Design, Publication Status, Non-human
574 | Li LB, Wang N, Wu XL, Wang L, Li JJ, Yang M, Ma J. Energy Balance-related Behaviors Are Related to Cardiometabolic Parameters and Predict Adiposity in 8-14-year-old Overweight Chinese Children One Year Later. Biomed Environ Sci. 2016. 29:754–757 https://www.ncbi.nlm.nih.gov/pubmed/27927275 | Intervention/Exposure
575 | Lindvall K, Jenkins P, Scribani M, Emmelin M, Larsson C, Norberg M, Weinehall L. Comparisons of weight change, eating habits and physical activity between women in Northern Sweden and Rural New York State- results from a longitudinal study. Nutr J. 2015. 14:88 https://www.ncbi.nlm.nih.gov/pubmed/26319494 | Intervention/Exposure
576 | Lipsky LM, Haynie DL, Liu D, Chaurasia A, Gee B, Li K, Iannotti RJ, Simons-Morton B. Trajectories of eating behaviors in a nationally representative cohort of U.S. adolescents during the transition to young adulthood. Int J Behav Nutr Phys Act. 2015. 12:138 https://www.ncbi.nlm.nih.gov/pubmed/26537771 | Intervention/Exposure, Daily Eating Occasions Not Reported
577 | Liu B, Hutchison AT, Thompson CH, Lange K, Heilbronn LK. Markers of adipose tissue inflammation are transiently elevated during intermittent fasting in women who are overweight or obese. Obes Res Clin Pract. 2019. 13:408–415 https://www.ncbi.nlm.nih.gov/pubmed/31302012 | Intervention/Exposure
578 | Liu B, Hutchison AT, Thompson CH, Wittert GA, Heilbronn L. Adipose tissue remodeling following eight-week calorie restriction or intermittent fasting in females who are overweight and obese. Diabetes. 2017. 66:A550 | Study Design, Publication Status
579 | Liu J, Hay J, Faught BE, Wade T, Cairney J, Merchant AT, Trevisan M. Family eating and activity habits, diet quality and pre-adolescent overweight and obesity. Public Health. 2012. 126:532–4 https://www.ncbi.nlm.nih.gov/pubmed/22560409 | Study Design, Intervention/Exposure, Publication Status
580 | Lofthouse M. School dinners and cardiovascular risk. Nature Clinical Practice Endocrinology and Metabolism. 2006. 2:8–9 | Publication Status
581 | Lojko D, Stelmach-Mardas M, Suwalska A. Diet quality and eating patterns in euthymic bipolar patients. Eur Rev Med Pharmacol Sci. 2019. 23:1221–1238 https://www.ncbi.nlm.nih.gov/pubmed/30779092 | Study Design
582 | Lombardo M, Bellia A, Padua E, Annino G, Guglielmi V, D’Adamo M, Iellamo F, Sbraccia P. Morning meal more efficient for fat loss in a 3-month lifestyle intervention. J Am Coll Nutr. 2014. 33:198–205 https://www.ncbi.nlm.nih.gov/pubmed/24809437 | Comparator, Size of Study Groups
583 | Lopez Minguez J, Saxena R, Bandin Saura C, Scheer F, Garaulet Aza M. Dinner timing interacts with MTNR1B SNP to influence glucose tolerance in natural late eaters. Sleep. 2016. 39:A51–A52 | Study Design, Publication Status
584 | Lopez-Bueno M, Gonzalez-Jimenez E, Navarro-Prado S, Montero-Alonso MA, Schmidt-RioValle J. Influence of age and religious fasting on the body composition of Muslim women living in a westernized context. Nutr Hosp. 2014. 31:1067–73 https://www.ncbi.nlm.nih.gov/pubmed/25726194 | Intervention/Exposure, Daily Eating Occasions Not Reported
585 | López-Bueno M, González-Jiménez E, Navarro-Prado S, Montero-Alonso MA, Schmidt-RioValle J. Influence of age and religious fasting on the body composition of Muslim women living in a westernized context. Nutrición hospitalaria. 2015. 31:1067–1073 | Daily Eating Occasions Not Reported
586 | Lopez-Minguez J, Saxena R, Bandin C, Scheer FA, Garaulet M. Late dinner impairs glucose tolerance in MTNR1B risk allele carriers: A randomized, cross-over study. Clin Nutr. 2018. 37:1133–1140 https://www.ncbi.nlm.nih.gov/pubmed/28455106 | Intervention/Exposure, Daily Eating Occasions Not Reported, Comparator
587 | Lopez-Olmedo N, Hernandez-Cordero S, Neufeld LM, Garcia-Guerra A, Mejia-Rodriguez F, Mendez Gomez-Humaran I. The Associations of Maternal Weight Change with Breastfeeding, Diet and Physical Activity During the Postpartum Period. Matern Child Health J. 2016. 20:270–80 https://www.ncbi.nlm.nih.gov/pubmed/26525558 | Intervention/Exposure
588 | Loy SL, Cheng TS, Colega MT, Cheung YB, Godfrey KM, Gluckman PD, Kwek K, Saw SM, Chong YS, Padmapriya N, Muller-Riemenschneider F, Lek N, Yap F, Chong MF, Chan JKY. Predominantly night-time feeding and maternal glycaemic levels during pregnancy. Br J Nutr. 2016. 115:1563–1570 https://www.ncbi.nlm.nih.gov/pubmed/26949026 | Daily Eating Occasions Not Reported
589 | Lucassen EA, Zhao X, Rother KI, Mattingly MS, Courville AB, de Jonge L, Csako G, Cizza G. Evening chronotype is associated with changes in eating behavior, more sleep apnea, and increased stress hormones in short sleeping obese individuals. PLoS One. 2013. 8:e56519 https://www.ncbi.nlm.nih.gov/pubmed/23483886 | Daily Eating Occasions Not Reported
590 | Maccario M, Aimaretti G, Corneli G, Gauna C, Grottoli S, Bidlingmaier M, Strasburger CJ, Dieguez C, Casanueva FF, Ghigo E. Short-term fasting abolishes the sex-related difference in GH and leptin secretion in humans. Am J Physiol Endocrinol Metab. 2000. 279:E411–6 https://www.ncbi.nlm.nih.gov/pubmed/10913042 | Study Design, Intervention/Exposure, Daily Eating Occasions Not Reported, Comparator
591 | Macdiarmid J, Loe J, Craig LC, Masson LF, Holmes B, McNeill G. Meal and snacking patterns of school-aged children in Scotland. Eur J Clin Nutr. 2009. 63:1297–304 https://www.ncbi.nlm.nih.gov/pubmed/19707230 | Study Design
592 | MacFarlane A, Cleland V, Crawford D, Campbell K, Timperio A. Longitudinal examination of the family food environment and weight status among children. Int J Pediatr Obes. 2009. 4:343–52 https://www.ncbi.nlm.nih.gov/pubmed/19922051 | Daily Eating Occasions Not Reported
593 | Madjd A, Taylor MA, Delavari A, Malekzadeh R, Macdonald IA, Farshchi HR. Beneficial effect of high energy intake at lunch rather than dinner on weight loss in healthy obese women in a weight-loss program: a randomized clinical trial. Am J Clin Nutr. 2016. 104:982–989 https://www.ncbi.nlm.nih.gov/pubmed/27581472 | Intervention/Exposure, Daily Eating Occasions Not Reported
594 | Madkour MI, El-Serafi A T, Jahrami HA, Sherif NM, Hassan RE, Awadallah S, Faris MAE. Ramadan diurnal intermittent fasting modulates SOD2, TFAM, Nrf2, and sirtuins (SIRT1, SIRT3) gene expressions in subjects with overweight and obesity. Diabetes Res Clin Pract. 2019. 155:107801 https://www.ncbi.nlm.nih.gov/pubmed/31356832 | Daily Eating Occasions Not Reported, Eating Frequency Data Collection
595 | Maffeis C, Provera S, Filippi L, Sidoti G, Schena S, Pinelli L, Tato L. Distribution of food intake as a risk factor for childhood obesity. Int J Obes Relat Metab Disord. 2000. 24:75–80 https://www.ncbi.nlm.nih.gov/pubmed/10702754 | Study Design
596 | Makarem N, Aggarwal B, Sears DD, St-Onge MP, Castaneda SF, Talavera GA, Marinac CR, Patterson R, Sotres-Alvarez D, Garcia ML, etal. Circadian timing of food intake is associated with cardiometabolic risk in us hispanics/latinos: results from the hispanic community health study/study of latinos. Circulation. 2018. 138(6 ). | Study Design, Publication Status
597 | Makvandi S, Karimi L, Mahdavian M, Bastami A. No Differences in Hematological Parameters of Fasting and Non-Fasting Pregnant Women Three Months after Ramadan. Int J Vitam Nutr Res. 2018. 88:258–262 https://www.ncbi.nlm.nih.gov/pubmed/31124419 | Outcome, Age: Outcome
598 | Malinauskas BM, Raedeke TD, Aeby VG, Smith JL, Dallas MB. Dieting practices, weight perceptions, and body composition: a comparison of normal weight, overweight, and obese college females. Nutr J. 2006. 5:11 https://www.ncbi.nlm.nih.gov/pubmed/16579846 | Study Design
599 | Marinac CR, Sears DD, Natarajan L, Gallo LC, Breen CI, Patterson RE. Frequency and Circadian Timing of Eating May Influence Biomarkers of Inflammation and Insulin Resistance Associated with Breast Cancer Risk. PLoS One. 2015. 10:e0136240 https://www.ncbi.nlm.nih.gov/pubmed/26305095 | Study Design
600 | Marlatt KL, Farbakhsh K, Dengel DR, Lytle LA. Breakfast and fast food consumption are associated with selected biomarkers in adolescents. Prev Med Rep. 2016. 3:49–52 https://www.ncbi.nlm.nih.gov/pubmed/26844187 | Study Design
601 | Marlatt KL, Redman LM, Burton JH, Martin CK, Ravussin E. Persistence of weight loss and acquired behaviors 2 y after stopping a 2-y calorie restriction intervention. Am J Clin Nutr. 2017. 105:928–935 https://www.ncbi.nlm.nih.gov/pubmed/28275127 | Intervention/Exposure, Size of Study Groups
602 | Marmonier C, Chapelot D, Fantino M, Louis-Sylvestre J. Snacks consumed in a nonhungry state have poor satiating efficiency: influence of snack composition on substrate utilization and hunger. American journal of clinical nutrition. 2002;76(3):518–28. https://www.ncbi.nlm.nih.gov/pubmed/12197994 | Daily Eating Occasions Not Reported, Size of Study Groups
603 | Martin J, MacDonald-Wicks L, Hure A, Smith R, Collins CE. Reducing postpartum weight retention and improving breastfeeding outcomes in overweight women: a pilot randomised controlled trial. Nutrients. 2015. 7:1464–79 https://www.ncbi.nlm.nih.gov/pubmed/25723973 | Intervention/Exposure, Daily Eating Occasions Not Reported
604 | Masheb RM, Grilo CM. Eating patterns and breakfast consumption in obese patients with binge eating disorder. Behav Res Ther. 2006. 44:1545–53 https://www.ncbi.nlm.nih.gov/pubmed/16376851 | Study Design
605 | Mathew S, Krug S, Skurk T, Halama A, Stank A, Artati A, Prehn C, Malek JA, Kastenmuller G, Romisch-Margl W, Adamski J, Hauner H, Suhre K. Metabolomics of Ramadan fasting: an opportunity for the controlled study of physiological responses to food intake. J Transl Med. 2014. 12:161 https://www.ncbi.nlm.nih.gov/pubmed/24906381 | Daily Eating Occasions Not Reported
606 | Mattson MP. The need for controlled studies of the effects of meal frequency on health. Lancet. 2005. 365:1978–80 https://www.ncbi.nlm.nih.gov/pubmed/15936428 | Study Design
607 | Maughan RJ, Bartagi Z, Dvorak J, Zerguini Y. Dietary intake and body composition of football players during the holy month of Ramadan. J Sports Sci. 2008. 26 Suppl 3:S29–38 https://www.ncbi.nlm.nih.gov/pubmed/19085450 | Intervention/Exposure, Daily Eating Occasions Not Reported
608 | Maukonen M, Kanerva N, Partonen T, Mannisto S. Chronotype and energy intake timing in relation to changes in anthropometrics: a 7-year follow-up study in adults. Chronobiol Int. 2019. 36:27–41 https://www.ncbi.nlm.nih.gov/pubmed/30212231 | Daily Eating Occasions Not Reported
609 | Mazurak N, Gunther A, Grau FS, Muth ER, Pustovoyt M, Bischoff SC, Zipfel S, Enck P. Effects of a 48-h fast on heart rate variability and cortisol levels in healthy female subjects. Eur J Clin Nutr. 2013. 67:401–6 https://www.ncbi.nlm.nih.gov/pubmed/23403876 | Intervention/Exposure, Daily Eating Occasions Not Reported
610 | McCaffree J. Childhood eating patterns: the roles parents play. J Am Diet Assoc. 2003. 103:1587 https://www.ncbi.nlm.nih.gov/pubmed/14647078 | Study Design
611 | McCrory MA, Howarth NC, Roberts SB, Huang TT. Eating frequency and energy regulation in free-living adults consuming self-selected diets. Journal of Nutrition. 2011. 141:148–153 | Study Design
612 | McDonald L, Wardle J, Llewellyn CH, Johnson L, van Jaarsveld CH, Syrad H, Fisher A. Sleep and nighttime energy consumption in early childhood: a population-based cohort study. Pediatr Obes. 2015. 10:454–60 https://www.ncbi.nlm.nih.gov/pubmed/25565402 | Intervention/Exposure, Daily Eating Occasions Not Reported, Comparator
613 | McGiveron A, Foster S, Pearce J, Taylor MA, McMullen S, Langley-Evans SC. Limiting antenatal weight gain improves maternal health outcomes in severely obese pregnant women: findings of a pragmatic evaluation of a midwife-led intervention. J Hum Nutr Diet. 2015. 28 Suppl 1:29–37 https://www.ncbi.nlm.nih.gov/pubmed/24809211 | Intervention/Exposure
614 | McIver VJ, Mattin LR, Evans GH, Yau AMW. Diurnal influences of fasted and non-fasted brisk walking on gastric emptying rate, metabolic responses, and appetite in healthy males. Appetite. 2019. 143:104411 https://www.ncbi.nlm.nih.gov/pubmed/31445052 | Intervention/Exposure
615 | McNeil J, Mamlouk MM, Duval K, Schwartz A, Nardo Junior N, Doucet E. Alterations in metabolic profile occur in normal-weight and obese men during the Ramadan fast despite no changes in anthropometry. J Obes. 2014. 2014:482547 https://www.ncbi.nlm.nih.gov/pubmed/25177497 | Daily Eating Occasions Not Reported
616 | Megson M, Wing R, Leahey TM. Effects of breakfast eating and eating frequency on body mass index and weight loss outcomes in adults enrolled in an obesity treatment program. J Behav Med. 2017. 40:595–601 https://www.ncbi.nlm.nih.gov/pubmed/28110468 | Eating Frequency Data Collection
617 | Mejean C, Lampure A, Si Hassen W, Gojard S, Peneau S, Hercberg S, Castetbon K. Influence of food preparation behaviors on 5-year weight change and obesity risk in a French prospective cohort. Int J Behav Nutr Phys Act. 2018. 15:120 https://www.ncbi.nlm.nih.gov/pubmed/30477513 | Intervention/Exposure
618 | Mekary RA. Breakfast Skipping and Type 2 Diabetes: Where Do We Stand?. J Nutr. 2019. 149:1–3 https://www.ncbi.nlm.nih.gov/pubmed/30624661 | Study Design, Publication Status
619 | Memari A-H, Kordi R, Panahi N, Nikookar LR, Abdollahi M, Akbarnejad A. Effect of Ramadan Fasting on Body Composition and Physical Performance in Female Athletes. Asian Journal of Sports Medicine. 2011;2(3):161–6. https://www.ncbi.nlm.nih.gov/pubmed/22375235. | Daily Eating Occasions Not Reported
620 | Mendez-Hernandez P, Dosamantes-Carrasco LD, Siani C, Pierlot R, Martinez-Gomez M, Rivera-Paredez B, et al. Mealtime habits and risk of developing the metabolic syndrome or insulin resistance among Mexican adults. Br J Nutr. 2016:1–10. https://www.ncbi.nlm.nih.gov/pubmed/27842612. | Intervention/Exposure
621 | Menon JE, Stensel DJ, Tolfrey K, Burns SF. Increased Meal Frequency With Exercise Mitigates Postprandial Triacylglycerol. J Phys Act Health. 2019. 16:589–594 https://www.ncbi.nlm.nih.gov/pubmed/31195871 | Daily Eating Occasions Not Reported, Eating Frequency Data Collection
622 | Merl V, Peters A, Oltmanns KM, Kern W, Hubold C, Hallschmid M, Born J, Fehm HL, Schultes B. Preserved circadian rhythm of serum insulin concentration at low plasma glucose during fasting in lean and overweight humans. Metabolism. 2004. 53:1449–53 https://www.ncbi.nlm.nih.gov/pubmed/15536600 | Daily Eating Occasions Not Reported
623 | Merten MJ, Williams AL, Shriver LH. Breakfast consumption in adolescence and young adulthood: parental presence, community context, and obesity. J Am Diet Assoc. 2009. 109:1384–91 https://www.ncbi.nlm.nih.gov/pubmed/19631044 | Daily Eating Occasions Not Reported
624 | Mi SJ, Kelly NR, Brychta RJ, Grammer AC, Jaramillo M, Chen KY, Fletcher LA, Bernstein SB, Courville AB, Shank LM, Pomeroy JJ, Brady SM, Broadney MM, Tanofsky-Kraff M, Yanovski JA. Associations of sleep patterns with metabolic syndrome indices, body composition, and energy intake in children and adolescents. Pediatr Obes. 2019. 14:e12507 https://www.ncbi.nlm.nih.gov/pubmed/30702801 | Intervention/Exposure
625 | Micali N, Ploubidis G, De Stavola B, Simonoff E, Treasure J. Frequency and patterns of eating disorder symptoms in early adolescence. J Adolesc Health. 2014. 54:574–81 https://www.ncbi.nlm.nih.gov/pubmed/24360247 | Intervention/Exposure
626 | Michalsen A, Frey UH, Merse S, Siffert W, Dobos GJ. Hunger and mood during extended fasting are dependent on the GNB3 C825T polymorphism. Ann Nutr Metab. 2009. 54:184–8 https://www.ncbi.nlm.nih.gov/pubmed/19420911 | Study Design, Intervention/Exposure, Daily Eating Occasions Not Reported
627 | Michalsen A, Hoffmann B, Moebus S, Bcker M, Langhorst J, Dobos GJ. Incorporation of fasting therapy in an integrative medicine ward: evaluation of outcome, safety, and effects on lifestyle adherence in a large prospective cohort study [corrected] [published erratum appears in J Altern Complement Med 2005 Dec;11(6):1121]. Journal of Alternative & Complementary Medicine. 2005;11(4):601–7. https://www.ncbi.nlm.nih.gov/pubmed/16131283. | Health Status
628 | Michalsen A, Kuhlmann MK, Ludtke R, Backer M, Langhorst J, Dobos GJ. Prolonged fasting in patients with chronic pain syndromes leads to late mood-enhancement not related to weight loss and fasting-induced leptin depletion. Nutr Neurosci. 2006. 9:195–200 https://www.ncbi.nlm.nih.gov/pubmed/17263085 | Daily Eating Occasions Not Reported
629 | Michalsen A, Schlegel F, Rodenbeck A, Ludtke R, Huether G, Teschler H, Dobos GJ. Effects of short-term modified fasting on sleep patterns and daytime vigilance in non-obese subjects: results of a pilot study. Ann Nutr Metab. 2003. 47:194–200 https://www.ncbi.nlm.nih.gov/pubmed/12748412 | Outcome
630 | Michalsen A, Schneider S, Rodenbeck A, Ludtke R, Huether G, Dobos GJ. The short-term effects of fasting on the neuroendocrine system in patients with chronic pain syndromes. Nutr Neurosci. 2003. 6:11–8 https://www.ncbi.nlm.nih.gov/pubmed/12608732 | Intervention/Exposure, Daily Eating Occasions Not Reported
631 | Mielgo-Ayuso J, Valtuena J, Cuenca-Garcia M, Gottrand F, Breidenassel C, Ferrari M, Manios Y, De Henauw S, Widhalm K, Kafatos A, Kersting M, Huybrechts I, Moreno LA, Gonzalez-Gross M. Regular breakfast consumption is associated with higher blood vitamin status in adolescents: the HELENA (Healthy Lifestyle in Europe by Nutrition in Adolescence) Study. Public Health Nutr. 2017. 20:1393–1404 https://www.ncbi.nlm.nih.gov/pubmed/28183371 | Study Design
632 | Min C, Noh H, Kang YS, Sim HJ, Baik HW, Song WO, Yoon J, Park YH, Joung H. Skipping breakfast is associated with diet quality and metabolic syndrome risk factors of adults. Nutr Res Pract. 2011. 5:455–63 https://www.ncbi.nlm.nih.gov/pubmed/22125684 | Study Design, Daily Eating Occasions Not Reported
633 | Miranda ER, Varady K, Haus JM. Weight loss via alternate day fasting increases circulating endogenous secretory RAGE and is associated with markers of adipocyte health. FASEB journal. 2017;31(1). | Study Design, Publication Status
634 | Miyamoto S, Murotani K, Yanagawa T, Kato A, Matsunaga S. Relationship of low lean body mass with body weight increase until one year of age and current lifestyles in Japanese young women. J Hum Ergol (Tokyo). 2010. 39:45–51 https://www.ncbi.nlm.nih.gov/pubmed/21922790 | Intervention/Exposure
635 | Mojto V, Gvozdjakova A, Kucharska J, Rausova Z, Vancova O, Valuch J. Effects of complete water fasting and regeneration diet on kidney function, oxidative stress and antioxidants. Bratisl Lek Listy. 2018. 119:107–111 https://www.ncbi.nlm.nih.gov/pubmed/29455546 | Study Design, Intervention/Exposure, Size of Study Groups
636 | Mok A, Haldar S, Lee JC, Leow MK, Henry CJ. Postprandial changes in cardiometabolic disease risk in young Chinese men following isocaloric high or low protein diets, stratified by either high or low meal frequency - a randomized controlled crossover trial. Nutr J. 2016. 15:27 https://www.ncbi.nlm.nih.gov/pubmed/26979583 | Eating Frequency Data Collection
637 | Moller L, Stodkilde-Jorgensen H, Jensen FT, Jorgensen JO. Fasting in healthy subjects is associated with intrahepatic accumulation of lipids as assessed by 1H-magnetic resonance spectroscopy. Clin Sci (Lond). 2008. 114:547–52 https://www.ncbi.nlm.nih.gov/pubmed/17990983 | Intervention/Exposure, Daily Eating Occasions Not Reported
638 | Molzof HE, Wirth MD, Burch JB, Shivappa N, Hebert JR, Johnson RL, Gamble KL. The impact of meal timing on cardiometabolic syndrome indicators in shift workers. Chronobiol Int. 2017. 34:337–348 https://www.ncbi.nlm.nih.gov/pubmed/28107043 | Study Design
639 | Moosavi SA, Kabir A, Moghimi A, Chehrei A, Rad MB. Evaluation of the effect of Islamic fasting on lung volumes and capacities in the healthy persons. Saudi Med J. 2007. 28:1666–70 https://www.ncbi.nlm.nih.gov/pubmed/17965786 | Outcome
640 | Morgan LM, Shi JW, Hampton SM, Frost G. Effect of meal timing and glycaemic index on glucose control and insulin secretion in healthy volunteers. Br J Nutr. 2012. 108:1286–91 https://www.ncbi.nlm.nih.gov/pubmed/22176632 | Comparator
641 | Morimoto A, Ohno Y, Tatsumi Y, Mizuno S, Watanabe S. Effects of healthy dietary pattern and other lifestyle factors on incidence of diabetes in a rural Japanese population. Asia Pac J Clin Nutr. 2012. 21:601–8 https://www.ncbi.nlm.nih.gov/pubmed/23017319 | Daily Eating Occasions Not Reported
642 | Moro T, Tinsley G, Bianco A, Marcolin G, Pacelli QF, Battaglia G, Palma A, Gentil P, Neri M, Paoli A. Effects of eight weeks of time-restricted feeding (16/8) on basal metabolism, maximal strength, body composition, inflammation, and cardiovascular risk factors in resistance-trained males. J Transl Med. 2016. 14:290 https://www.ncbi.nlm.nih.gov/pubmed/27737674 | Comparator
643 | Morris CJ, Purvis TE, Mistretta J, Scheer FA. Effects of the Internal Circadian System and Circadian Misalignment on Glucose Tolerance in Chronic Shift Workers. J Clin Endocrinol Metab. 2016. 101:1066–74 https://www.ncbi.nlm.nih.gov/pubmed/26771705 | Comparator
644 | Mostad IL, Langaas M, Grill V. Central obesity is associated with lower intake of whole-grain bread and less frequent breakfast and lunch: results from the HUNT study, an adult all-population survey. Appl Physiol Nutr Metab. 2014;39(7):819–28. https://www.ncbi.nlm.nih.gov/pubmed/24833275. | Study Design
645 | Mota J, Fidalgo F, Silva R, Ribeiro JC, Santos R, Carvalho J, Santos MP. Relationships between physical activity, obesity and meal frequency in adolescents. Ann Hum Biol. 2008. 35:1–10 https://www.ncbi.nlm.nih.gov/pubmed/18274921 | Study Design
646 | Mota MC, Silva CM, Balieiro LCT, Goncalves BF, Fahmy WM, Crispim CA. Association between social jetlag food consumption and meal times in patients with obesity-related chronic diseases. PLoS One. 2019. 14:e0212126 https://www.ncbi.nlm.nih.gov/pubmed/30753224 | Study Design, Intervention/Exposure, Daily Eating Occasions Not Reported
647 | Motohashi Y, Higuchi S, Ahara M, Kaneko Y. Sleep time and working conditions of office workers. Sleep and Biological Rhythms. 2003. 1:131–132 | Study Design, Intervention/Exposure
648 | Mughal F. Ramadan: what it means for general practice. Br J Gen Pract. 2014. 64:356 https://www.ncbi.nlm.nih.gov/pubmed/24982480 | Study Design
649 | Munkholm A, Olsen EM, Rask CU, Clemmensen L, Rimvall MK, Jeppesen P, Micali N, Skovgaard AM. Early Predictors of Eating Problems in Preadolescence-A Prospective Birth Cohort Study. J Adolesc Health. 2016. 58:533–42 https://www.ncbi.nlm.nih.gov/pubmed/27107908 | Intervention/Exposure, Daily Eating Occasions Not Reported
650 | Munoz JSG, Canavate R, Hernandez CM, Cara-Salmeron V, Morante JJH. The association among chronotype, timing of food intake and food preferences depends on body mass status. Eur J Clin Nutr. 2017. 71:736–742 https://www.ncbi.nlm.nih.gov/pubmed/27650874 | Intervention/Exposure, Daily Eating Occasions Not Reported
651 | Munsters MJ, Saris WH. Effects of meal frequency on metabolic profiles and substrate partitioning in lean healthy males. PLoS One. 2012. 7:e38632 https://www.ncbi.nlm.nih.gov/pubmed/22719910 | Size of Study Groups
652 | Murakami K, Livingstone MB. Associations between meal and snack frequency and diet quality and adiposity measures in British adults: findings from the National Diet and Nutrition Survey. Public Health Nutr. 2016. 19:1624–34 https://www.ncbi.nlm.nih.gov/pubmed/26471309 | Study Design
653 | Murakami K, Livingstone MBE, Sasaki S. Establishment of a Meal Coding System for the Characterization of Meal-Based Dietary Patterns in Japan. J Nutr. 2017. 147:2093–2101 https://www.ncbi.nlm.nih.gov/pubmed/28904121 | Study Design, Outcome
654 | Musaiger AO, Al-Roomi K, Bader Z. Social, dietary and lifestyle factors associated with obesity among Bahraini adolescents. Appetite. 2014. 73:197–204 https://www.ncbi.nlm.nih.gov/pubmed/24231426 | Study Design
655 | Mzoughi K, Zairi I, Jabeur M, Kraiem S. The effects of fasting on heart rate variability in hypertensive patients. Clin Exp Hypertens. 2018. 40:793–796 https://www.ncbi.nlm.nih.gov/pubmed/29420093 | Health Status
656 | Mzoughi K, Zairi I, Jabeur M, Zoghlemi B, Mimouni N, Ben Moussa F, Kamoun S, Fennira S, Kraiem S. P-207: The effects of Ramadan Fasting on heart rate variability in hypertensive patients. Annales de Cardiologie et dAngeiologie. 2015. 64:S92 | Daily Eating Occasions Not Reported, Publication Status
657 | Nagai M, Uyama O, Kaji H. Dietary habits prone to lifestyle-related disease. Health Education Journal. 2013. 72:172–179 | Study Design
658 | Nagata JM, Garber AK, Tabler J, Murray SB, Vittinghoff E, Bibbins-Domingo K. Disordered eating behaviors and cardiometabolic risk among young adults with overweight or obesity. Int J Eat Disord. 2018. 51:931–941 https://www.ncbi.nlm.nih.gov/pubmed/30030944 | Intervention/Exposure, Daily Eating Occasions Not Reported
659 | Nagata K, Yoshida M, Ishimoto Y, Hashizume H, Yamada H, Yoshimura N. Skipping breakfast and less exercise are risk factors for bone loss in young Japanese adults: a 3-year follow-up study. J Bone Miner Metab. 2014. 32:420–7 https://www.ncbi.nlm.nih.gov/pubmed/24052206 | Daily Eating Occasions Not Reported
660 | Naharudin MNB, Yusof A. The effect of 10 days of intermittent fasting on Wingate anaerobic power and prolonged high-intensity time-to-exhaustion cycling performance. Eur J Sport Sci. 2018. 18:667–676 https://www.ncbi.nlm.nih.gov/pubmed/29485326 | Size of Study Groups
661 | Nakajima K, Suwa K. Association of hyperglycemia in a general Japanese population with late-night-dinner eating alone, but not breakfast skipping alone. J Diabetes Metab Disord. 2015. 14:16 https://www.ncbi.nlm.nih.gov/pubmed/25874189 | Study Design
662 | Nas A, Hagele F, Kahlhofer J, Keller J, Rising R, Bosy-Westphal A. Impact of breakfast skipping vs. dinner skipping on regulation of energy balance and metabolic risk. Obesity facts. 2017. 10:76 | Publication Status
663 | Nas A, Mirza N, Hagele F, Kahlhofer J, Keller J, Rising R, Kufer TA, Bosy-Westphal A. Impact of breakfast skipping compared with dinner skipping on regulation of energy balance and metabolic risk. Am J Clin Nutr. 2017. 105:1351–1361 https://www.ncbi.nlm.nih.gov/pubmed/28490511 | Eating Frequency Data Collection
664 | Neel F. Do you know how important your eating habits are to your health? Eating less + exercising more = better health. J Ky Med Assoc. 2007. 105:223–4 https://www.ncbi.nlm.nih.gov/pubmed/17566468 | Study Design
665 | Nematy M, Alinezhad-Namaghi M, Rashed MM, Mozhdehifard M, Sajjadi SS, Akhlaghi S, Sabery M, Mohajeri SA, Shalaey N, Moohebati M, Norouzy A. Effects of Ramadan fasting on cardiovascular risk factors: a prospective observational study. Nutr J. 2012. 11:69 https://www.ncbi.nlm.nih.gov/pubmed/22963582 | Daily Eating Occasions Not Reported
666 | Nemet D, Barzilay-Teeni N, Eliakim A. Treatment of childhood obesity in obese families. J Pediatr Endocrinol Metab. 2008. 21:461–7 https://www.ncbi.nlm.nih.gov/pubmed/18655528 | Study Design, Intervention/Exposure
667 | Neumann BL, Dunn A, Johnson D, Adams JD, Baum JI. Breakfast Macronutrient Composition Influences Thermic Effect of Feeding and Fat Oxidation in Young Women Who Habitually Skip Breakfast. Nutrients. 2016;8(8). https://www.ncbi.nlm.nih.gov/pubmed/27517958. | Daily Eating Occasions Not Reported
668 | Neumark-Sztainer D, Wall M, Haines J, Story M, Eisenberg ME. Why does dieting predict weight gain in adolescents? Findings from project EAT-II: a 5-year longitudinal study. J Am Diet Assoc. 2007. 107:448–55 https://www.ncbi.nlm.nih.gov/pubmed/17324664 | Intervention/Exposure, Daily Eating Occasions Not Reported
669 | Neumark-Sztainer DR, Wall MM, Haines JI, Story MT, Sherwood NE, van den Berg PA. Shared risk and protective factors for overweight and disordered eating in adolescents. Am J Prev Med. 2007. 33:359–369 https://www.ncbi.nlm.nih.gov/pubmed/17950400 | Intervention/Exposure, Daily Eating Occasions Not Reported
670 | Nicklas TA, ONeil CE, Fulgoni VL. Snacking patterns, diet quality, and cardiovascular risk factors in adults. BMC Public Health. 2014. 14:388 https://www.ncbi.nlm.nih.gov/pubmed/24754905 | Study Design
671 | Niemeier BS, Hektner JM. Weight-Related Health Behaviors and Body Mass: Associations between Young Adults and Their Parents, Moderated by Parental Authority. American Journal of Health Education. 2012;43(6):366–77. | Study Design
672 | Niemeier HM, Raynor HA, Lloyd-Richardson EE, Rogers ML, Wing RR. Fast food consumption and breakfast skipping: predictors of weight gain from adolescence to adulthood in a nationally representative sample. J Adolesc Health. 2006. 39:842–9 https://www.ncbi.nlm.nih.gov/pubmed/17116514 | Daily Eating Occasions Not Reported
673 | Nishiura C, Noguchi J, Hashimoto H. Dietary patterns only partially explain the effect of short sleep duration on the incidence of obesity. Sleep. 2010. 33:753–7 https://www.ncbi.nlm.nih.gov/pubmed/20550015 | Intervention/Exposure, Daily Eating Occasions Not Reported
674 | Nisselson HS. The Perils of Skipping Breakfast. J N J Dent Assoc. 2015. 86:4 https://www.ncbi.nlm.nih.gov/pubmed/27156267 | Study Design, Daily Eating Occasions Not Reported
675 | Nola IA, Jelinic JD, Matanic D, Pucarin-Cvetkovic J, Bergman Markovic B, Senta A. Differences in eating and lifestyle habits between first- and sixth-year medical students from Zagreb. Coll Antropol. 2010. 34:1289–94 https://www.ncbi.nlm.nih.gov/pubmed/21874711 | Study Design
676 | Nomani MZ, Khan AH, Shahda MM, Nomani AK, Sattar SA. Predicting serum gastrin levels among men during Ramadan fasting. East Mediterr Health J. 2005. 11:119–25 https://www.ncbi.nlm.nih.gov/pubmed/16532680 | Daily Eating Occasions Not Reported
677 | Nonino-Borges CB, Martins Borges R, Bavaresco M, Suen VM, Moreira AC, Marchini JS. Influence of meal time on salivary circadian cortisol rhythms and weight loss in obese women. Nutrition. 2007. 23:385–91 https://www.ncbi.nlm.nih.gov/pubmed/17483007 | Comparator
678 | Nooyens AC, Visscher TL, Schuit AJ, van Rossum CT, Verschuren WM, van Mechelen W, Seidell JC. Effects of retirement on lifestyle in relation to changes in weight and waist circumference in Dutch men: a prospective study. Public Health Nutr. 2005. 8:1266–74 https://www.ncbi.nlm.nih.gov/pubmed/16372922 | Daily Eating Occasions Not Reported
679 | Norouzy A, Hasanzade Daloee M, Khoshnasab AH, Khoshnasab A, Farrokhi J, Nematy M, Safarian M, Nezafati P, Alinezhad-Namaghi M. Trend of blood pressure in hypertensive and normotensive volunteers during Ramadan fasting. Blood Press Monit. 2017. 22:253–257 https://www.ncbi.nlm.nih.gov/pubmed/28657936 | Study Design, Daily Eating Occasions Not Reported
680 | Norouzy A, Salehi M, Philippou E, Arabi H, Shiva F, Mehrnoosh S, Mohajeri SM, Mohajeri SA, Motaghedi Larijani A, Nematy M. Effect of fasting in Ramadan on body composition and nutritional intake: a prospective study. J Hum Nutr Diet. 2013. 26 Suppl 1:97–104 https://www.ncbi.nlm.nih.gov/pubmed/23679071 | Intervention/Exposure, Daily Eating Occasions Not Reported
681 | Norouzy A, Salehi M, Philippou E, Arabi H, Shiva F, Mehrnoosh S, Mohajeri SMR, Reza Mohajeri SA, Motaghedi Larijani A, Nematy M. Effect of fasting in Ramadan on body composition and nutritional intake: a prospective study. Journal of Human Nutrition & Dietetics. 2013. 26:97–104 | Daily Eating Occasions Not Reported
682 | Norrelund H, Nair KS, Nielsen S, Frystyk J, Ivarsen P, Jorgensen JO, Christiansen JS, Moller N. The decisive role of free fatty acids for protein conservation during fasting in humans with and without growth hormone. J Clin Endocrinol Metab. 2003. 88:4371–8 https://www.ncbi.nlm.nih.gov/pubmed/12970312 | Intervention/Exposure, Size of Study Groups
683 | Norrelund H, Nielsen S, Christiansen JS, Jorgensen JO, Moller N. Modulation of basal glucose metabolism and insulin sensitivity by growth hormone and free fatty acids during short-term fasting. Eur J Endocrinol. 2004. 150:779–87 https://www.ncbi.nlm.nih.gov/pubmed/15191347 | Intervention/Exposure, Daily Eating Occasions Not Reported
684 | Norton L, Parr T, Bardsley RG, Ye H, Tsintzas K. Characterization of GLUT4 and calpain expression in healthy human skeletal muscle during fasting and refeeding. Acta Physiol (Oxf). 2007. 189:233–40 https://www.ncbi.nlm.nih.gov/pubmed/17305703 | Study Design, Intervention/Exposure, Daily Eating Occasions Not Reported
685 | Novaes JF, Franceschini Sdo C, Priore SE. Mother’s overweight, parents’ constant limitation on the foods and frequent snack as risk factors for obesity among children in Brazil. Arch Latinoam Nutr. 2008. 58:256–64 https://www.ncbi.nlm.nih.gov/pubmed/19137988 | Study Design
686 | Nugraha B, Ghashang SK, Hamdan I, Gutenbrunner C. Effect of Ramadan fasting on fatigue, mood, sleepiness, and health-related quality of life of healthy young men in summer time in Germany: A prospective controlled study. Appetite. 2017. 111:38–45 https://www.ncbi.nlm.nih.gov/pubmed/28027907 | Daily Eating Occasions Not Reported, Size of Study Groups
687 | Nurul-Fadhilah A, Teo PS, Huybrechts I, Foo LH. Infrequent breakfast consumption is associated with higher body adiposity and abdominal obesity in Malaysian school-aged adolescents. PLoS One. 2013. 8:e59297 https://www.ncbi.nlm.nih.gov/pubmed/23520556 | Study Design
688 | Nygaard EB, Orskov C, Almdal T, Vestergaard H, Andersen B. Fasting decreases plasma FGF21 in obese subjects and the expression of FGF21 receptors in adipose tissue in both lean and obese subjects. J Endocrinol. 2018. 239:73–80 https://www.ncbi.nlm.nih.gov/pubmed/30307155 | Daily Eating Occasions Not Reported, Size of Study Groups
689 | O’Brien EC, Geraghty AA, O’Sullivan EJ, Riordan JA, Horan MK, Larkin E, Donnelly J, Mehegan J, Twomey PJ, McAuliffe FM. Five-year follow up of a low glycaemic index dietary randomised controlled trial in pregnancy-no long-term maternal effects of a dietary intervention. Bjog. 2019. 126:514–524 https://www.ncbi.nlm.nih.gov/pubmed/30303614 | Intervention/Exposure, Daily Eating Occasions Not Reported
690 | Odegaard AO, Jacobs DR, Steffen LM, Van Horn L, Ludwig DS, Pereira MA. Breakfast frequency and development of metabolic risk. Diabetes Care. 2013. 36:3100–6 https://www.ncbi.nlm.nih.gov/pubmed/23775814 | Daily Eating Occasions Not Reported
691 | Ödlund Olin A, Koochek A, Cederholm T, Ljungqvist O. Minimal effect on energy intake by additional evening meal for frail elderly service flat residents--a pilot study. J Nutr Health Aging. 2008;12(5):295–301. https://www.ncbi.nlm.nih.gov/pubmed/18443710. | Daily Eating Occasions Not Reported
692 | Ogata H, Hatamoto Y, Goto Y, Tajiri E, Yoshimura E, Kiyono K, Uehara Y, Kawanaka K, Omi N, Tanaka H. Association between breakfast skipping and postprandial hyperglycaemia after lunch in healthy young individuals. Br J Nutr. 2019. 122:431–440 https://www.ncbi.nlm.nih.gov/pubmed/31486356 | Daily Eating Occasions Not Reported, Eating Frequency Data Collection
693 | Ogata H, Kayaba M, Tanaka Y, Yajima K, Iwayama K, Ando A, et al. Effect of skipping breakfast for 6 days on energy metabolism and diurnal rhythm of blood glucose in young healthy Japanese males. Am J Clin Nutr. 2019. https://www.ncbi.nlm.nih.gov/pubmed/31095288. | Eating Frequency Data Collection
694 | Ohkawara K, Cornier MA, Kohrt WM, Melanson EL. Effects of increased meal frequency on fat oxidation and perceived hunger. Obesity (Silver Spring). 2013. 21:336–43 https://www.ncbi.nlm.nih.gov/pubmed/23404961 | Eating Frequency Data Collection
695 | Okada C, Imano H, Muraki I, Yamada K, Iso H. The Association of Having a Late Dinner or Bedtime Snack and Skipping Breakfast with Overweight in Japanese Women. J Obes. 2019. 2019:2439571 https://www.ncbi.nlm.nih.gov/pubmed/30944735 | Study Design
696 | Okada C, Imano H, Yamagishi K, Cui R, Umesawa M, Maruyama K, Muraki I, Hayama-Terada M, Shimizu Y, Sankai T, Okada T, Kiyama M, Kitamura A, Iso H. Dietary Intake of Energy and Nutrients from Breakfast and Risk of Stroke in The Japanese Population: The Circulatory Risk in Communities Study (CIRCS). J Atheroscler Thromb. 2019. 26:145–153 https://www.ncbi.nlm.nih.gov/pubmed/29899172 | Daily Eating Occasions Not Reported
697 | Okada C, Tabuchi T, Iso H. Association between skipping breakfast in parents and children and childhood overweight/obesity among children: a nationwide 10.5-year prospective study in Japan. Int J Obes (Lond). 2018. 42:1724–1732 https://www.ncbi.nlm.nih.gov/pubmed/29686380 | Daily Eating Occasions Not Reported
698 | Olafsdottir AS, Johannsdottir SS, Arngrimsson SA, Johannsson E. Lifestyle intervention at sea changes body composition, metabolic profile and fitness. Public Health. 2012;126(10):888–90. https://www.ncbi.nlm.nih.gov/pubmed/22884861. | Intervention/Exposure, Daily Eating Occasions Not Reported
699 | Olejniczak D, Bugajec D, Staniszewska A, Panczyk M, Kielan A, Czerw A, Manczuk M, Juszczyk G, Skonieczna J, Brytek-Matera A. Risk assessment of night-eating syndrome occurrence in women in Poland, considering the obesity factor in particular. Neuropsychiatr Dis Treat. 2018. 14:1521–1526 https://www.ncbi.nlm.nih.gov/pubmed/29942130 | Study Design, Daily Eating Occasions Not Reported
700 | Olson CM, Strawderman MS, Hinton PS, Pearson TA. Gestational weight gain and postpartum behaviors associated with weight change from early pregnancy to 1 y postpartum. International journal of obesity. 2003;27(1):117–27. https://www.ncbi.nlm.nih.gov/pubmed/12532163. | Intervention/Exposure, Daily Eating Occasions Not Reported
701 | Olson J, Aldrich H, Callahan TJ, Matthews EE, Gance-Cleveland B. Characterization of Childhood Obesity and Behavioral Factors. J Pediatr Health Care. 2016. 30:444–52 https://www.ncbi.nlm.nih.gov/pubmed/26614274 | Daily Eating Occasions Not Reported, Eating Frequency Data Collection
702 | Ong KK. Summary of Factors Influencing Healthy Growth. Nestle Nutr Inst Workshop Ser. 2017. 87:197–199 https://www.ncbi.nlm.nih.gov/pubmed/28315899 | Publication Status
703 | O’Reardon JP, Ringel BL, Dinges DF, Allison KC, Rogers NL, Martino NS, Stunkard AJ. Circadian eating and sleeping patterns in the night eating syndrome. Obes Res. 2004. 12:1789–96 https://www.ncbi.nlm.nih.gov/pubmed/15601974 | Intervention/Exposure, Daily Eating Occasions Not Reported, Outcome
704 | Orra AA, Pires MM, Ferreira SR. Distinct breakfast patterns on satiety perception in individuals with weight excess. Arch Endocrinol Metab. 2016. 60:333–40 https://www.ncbi.nlm.nih.gov/pubmed/26910624 | Intervention/Exposure, Comparator
705 | Oshida H, Kutsuma A, Nakajima K. Associations of eating a late-evening meal before bedtime with low serum amylase and unhealthy conditions. J Diabetes Metab Disord. 2013. 12:53 https://www.ncbi.nlm.nih.gov/pubmed/24354901 | Daily Eating Occasions Not Reported
706 | Ostachowska-Gasior A, Piwowar M, Kwiatkowski J, Kasperczyk J, Skop-Lewandowska A. Breakfast and Other Meal Consumption in Adolescents from Southern Poland. Int J Environ Res Public Health. 2016;13(5). https://www.ncbi.nlm.nih.gov/pubmed/27136572. | Study Design
707 | Oyama M, Nakamura K, Tsuchiya Y, Yamamoto M. Unhealthy maternal lifestyle leads to rapid infant weight gain: prevention of future chronic diseases. Tohoku J Exp Med. 2009. 217:67–72 https://www.ncbi.nlm.nih.gov/pubmed/19155610 | Outcome
708 | Ozturk E, Balat O, Ugur MG, Yazicioglu C, Pence S, Erel O, Kul S. Effect of Ramadan fasting on maternal oxidative stress during the second trimester: a preliminary study. J Obstet Gynaecol Res. 2011. 37:729–33 https://www.ncbi.nlm.nih.gov/pubmed/21736666 | Daily Eating Occasions Not Reported
709 | Palla L, Almoosawi S. Diurnal Patterns of Energy Intake Derived via Principal Component Analysis and Their Relationship with Adiposity Measures in Adolescents: Results from the National Diet and Nutrition Survey RP (2008(-)2012). Nutrients. 2019;11(2). https://www.ncbi.nlm.nih.gov/pubmed/30781551. | Study Design
710 | Pallayova M, Zaghloul HB, Arora T, Choudhury SM, Omar OM, Chagoury OL, Taheri S. Investigating physiological glucose excursions before, during, and after Ramadan in adults without diabetes mellitus. Physiol Behav. 2017. 179:110–115 https://www.ncbi.nlm.nih.gov/pubmed/28577886 | Daily Eating Occasions Not Reported
711 | Palmer MA, Capra S, Baines SK. Association between eating frequency, weight, and health. Nutrition reviews. 2009;67(7):379–90. https://www.ncbi.nlm.nih.gov/pubmed/19566598. | Study Design
712 | Panagiotopoulos C, Riddell MC, Sellers EAC. Type 2 Diabetes in Children and Adolescents. Canadian Journal of Diabetes. 2013. 37:S163–S167. | Study Design
713 | Panizza CE, Lim U, Yonemori KM, Cassel KD, Wilkens LR, Harvie MN, et al. Effects of Intermittent Energy Restriction Combined with a Mediterranean Diet on Reducing Visceral Adiposity: A Randomized Active Comparator Pilot Study. Nutrients. 2019;11(6). https://www.ncbi.nlm.nih.gov/pubmed/31226790. | Daily Eating Occasions Not Reported
714 | Papakonstantinou E, Kechribari I, Mitrou P, Trakakis E, Vassiliadi D, Georgousopoulou E, Zampelas A, Kontogianni MD, Dimitriadis G. Effect of meal frequency on glucose and insulin levels in women with polycystic ovary syndrome: a randomised trial. Eur J Clin Nutr. 2016. 70:588–94 https://www.ncbi.nlm.nih.gov/pubmed/26862008 | Health Status
715 | Papakonstantinou E, Kechribari I, Mitrou P, Trakakis E, Vassiliadi D, Georgousopoulou E, Zampelas A, Kontogianni MD, Dimitriadis G. Effect of meal frequency on glucose levels in women with polycystic ovary syndrome: a randomized trial. Obesity facts. 2015. 8:73–74 | Health Status
716 | Papakonstantinou E, Kontogianni MD, Mitrou P, Magriplis E, Vassiliadi D, Nomikos T, Lambadiari V, Georgousopoulou E, Dimitriadis G. Effects of 6 vs 3 eucaloric meal patterns on glycaemic control and satiety in people with impaired glucose tolerance or overt type 2 diabetes: A randomized trial. Diabetes Metab. 2018. 44:226–234 https://www.ncbi.nlm.nih.gov/pubmed/29680359 | Eating Frequency Data Collection
717 | Papoutsou S, Briassoulis G, Hadjigeorgiou C, Savva SC, Solea T, Hebestreit A, Pala V, Sieri S, Kourides Y, Kafatos A, Tornaritis M. The combination of daily breakfast consumption and optimal breakfast choices in childhood is an important public health message. Int J Food Sci Nutr. 2014. 65:273–9 https://www.ncbi.nlm.nih.gov/pubmed/24512299 | Study Design, Daily Eating Occasions Not Reported
718 | Park EH, Oh MS, Kim S, Lee J, Kang KS. The Analysis of Factors Causing the High Prevalence of Child Obesity in Jeju Island. Pediatr Gastroenterol Hepatol Nutr. 2018. 21:127–133 https://www.ncbi.nlm.nih.gov/pubmed/29713610 | Study Design
719 | Park HJ, Lee J, Kim JM, Lee HA, Kim SH, Kim Y. A study of snack consumption, night-eating habits, and nutrient intake in gestational diabetes mellitus. Clin Nutr Res. 2013. 2:42–51 https://www.ncbi.nlm.nih.gov/pubmed/23431085 | Study Design, Intervention/Exposure, Daily Eating Occasions Not Reported
720 | Parkes KR. Demographic and lifestyle predictors of body mass index among offshore oil industry workers: crosssectional and longitudinal findings. Occup Med (Lond). 2003. 53:213–21 https://www.ncbi.nlm.nih.gov/pubmed/12724556 | Intervention/Exposure
721 | Parr EB, Devlin BL, Brennan L, Hawley JA. Controlled time-restricted eating alters ratings of hunger, but does not change fatigue and mood in men with overweight/obesity. Obesity facts. 2019. 12:260 | Publication Status
722 | Parr EB, Devlin BL, Brennan L, Hawley JA. Effects of time-restricted feeding on mood, hunger and fatigue. Obesity research & clinical practice. 2019. 13:245 | Publication Status
723 | Parretti HM, Aveyard P, Blannin A, Clifford SJ, Coleman SJ, Roalfe A, Daley AJ. Efficacy of water preloading before main meals as a strategy for weight loss in primary care patients with obesity: RCT. Obesity (Silver Spring). 2015. 23:1785–91 https://www.ncbi.nlm.nih.gov/pubmed/26237305 | Daily Eating Occasions Not Reported
724 | Partridge C. Unhealthy lifestyle in college students could lead to diabetes risk. Nephrol News Issues. 2007. 21:22, 25 https://www.ncbi.nlm.nih.gov/pubmed/17269261 | Study Design, Intervention/Exposure, Publication Status
725 | Pasqua IC, Moreno CR. The nutritional status and eating habits of shift workers: a chronobiological approach. Chronobiol Int. 2004. 21:949–60 https://www.ncbi.nlm.nih.gov/pubmed/15646241 | Intervention/Exposure, Daily Eating Occasions Not Reported
726 | Patterson RE, Laughlin GA, LaCroix AZ, Hartman SJ, Natarajan L, Senger CM, Martinez ME, Villasenor A, Sears DD, Marinac CR, Gallo LC. Intermittent Fasting and Human Metabolic Health. J Acad Nutr Diet. 2015. 115:1203–12 https://www.ncbi.nlm.nih.gov/pubmed/25857868 | Study Design
727 | Pauley AM, Hohman E, Savage JS, Rivera DE, Guo P, Leonard KS, Symons Downs D. Gestational Weight Gain Intervention Impacts Determinants of Healthy Eating and Exercise in Overweight/Obese Pregnant Women. J Obes. 2018. 2018:6469170 https://www.ncbi.nlm.nih.gov/pubmed/30364005 | Intervention/Exposure
728 | Pawlow LA, ONeil PM, Malcolm RJ. Night eating syndrome: effects of brief relaxation training on stress, mood, hunger, and eating patterns. Int J Obes Relat Metab Disord. 2003. 27:970–8 https://www.ncbi.nlm.nih.gov/pubmed/12861239 | Intervention/Exposure
729 | Pearcey SM, de Castro JM. Food intake and meal patterns of weight-stable and weight-gaining persons. Am J Clin Nutr. 2002. 76:107–12 https://www.ncbi.nlm.nih.gov/pubmed/12081823 | Study Design
730 | Pedersen E, Jennifer BKeoghJ, Kristina Petersen K, Peter M, Clifton P. Effects of intermittent compared to continuous energy restriction on weight loss and diet quality after one year. Obesity reviews. 2014. 15:142 | Publication Status
731 | Pedersen MH, Svart MV, Lebeck J, Bidlingmaier M, Stodkilde-Jorgensen H, Pedersen SB, Moller N, Jessen N, Jorgensen JOL. Substrate Metabolism and Insulin Sensitivity During Fasting in Obese Human Subjects: Impact of GH Blockade. J Clin Endocrinol Metab. 2017. 102:1340–1349 https://www.ncbi.nlm.nih.gov/pubmed/28324055 | Intervention/Exposure, Daily Eating Occasions Not Reported
732 | Pelkman CL, Heinbach RA, Rolls BJ. Reproductive hormones and eating behavior in young women. Appetite. 2000. 34:217–8 https://www.ncbi.nlm.nih.gov/pubmed/10744913 | Study Design
733 | Pentikainen S, Tanner H, Karhunen L, Kolehmainen M, Poutanen K, Pennanen K. Mobile Phone App for Self-Monitoring of Eating Rhythm: Field Experiment. JMIR Mhealth Uhealth. 2019. 7:e11490 https://www.ncbi.nlm.nih.gov/pubmed/30916657 | Outcome, Size of Study Groups
734 | Peos JJ, Helms ER, Fournier PA, Sainsbury A. Continuous versus intermittent moderate energy restriction for increased fat mass loss and fat free mass retention in adult athletes: protocol for a randomised controlled trial-the ICECAP trial (Intermittent versus Continuous Energy restriction Compared in an Athlete Population). BMJ Open Sport Exerc Med. 2018. 4:e000423 https://www.ncbi.nlm.nih.gov/pubmed/30364484 | Study Design, Intervention/Exposure, Daily Eating Occasions Not Reported
735 | Pereira JL, Felix PV, Mattei J, Fisberg RM. Differences over 12 Years in Food Portion Size and Association with Excess Body Weight in the City of Sao Paulo, Brazil. Nutrients. 2018;10(6). https://www.ncbi.nlm.nih.gov/pubmed/29848971. | Study Design
736 | Pereira MA, Erickson E, McKee P, Schrankler K, Raatz SK, Lytle LA, et al. Breakfast frequency and quality may affect glycemia and appetite in adults and children. Journal of nutrition. 2011;141(1):163–8. https://www.ncbi.nlm.nih.gov/pubmed/21123469. | Study Design
737 | Perk G, Ghanem J, Aamar S, Ben-Ishay D, Bursztyn M. The effect of the fast of Ramadan on ambulatory blood pressure in treated hypertensives. J Hum Hypertens. 2001. 15:723–5 https://www.ncbi.nlm.nih.gov/pubmed/11607803 | Intervention/Exposure, Daily Eating Occasions Not Reported
738 | Perrigue MM, Drewnowski A, Wang CY, Neuhouser ML. Higher Eating Frequency Does Not Decrease Appetite in Healthy Adults. J Nutr. 2016. 146:59–64 https://www.ncbi.nlm.nih.gov/pubmed/26561409 | Outcome, Size of Study Groups
739 | Perrigue MM, Drewnowski A, Wang CY, Song X, Kratz M, Neuhouser ML. Randomized Trial Testing the Effects of Eating Frequency on Two Hormonal Biomarkers of Metabolism and Energy Balance. Nutr Cancer. 2017. 69:56–63 https://www.ncbi.nlm.nih.gov/pubmed/27918854 | Eating Frequency Data Collection
740 | Perrigue MM, Kantor ED, Hastert TA, Patterson R, Potter JD, Neuhouser ML, White E. Eating frequency and risk of colorectal cancer. Cancer Causes Control. 2013. 24:2107–15 https://www.ncbi.nlm.nih.gov/pubmed/24057417 | Outcome
741 | Peterson CM. Intermittent Fasting Induces Weight Loss, but the Effects on Cardiometabolic Health are Modulated by Energy Balance. Obesity (Silver Spring). 2019. 27:11 https://www.ncbi.nlm.nih.gov/pubmed/30569643 | Study Design, Publication Status
742 | Petherick ES, Tuffnell D, Wright J. Experiences and outcomes of maternal Ramadan fasting during pregnancy: results from a sub-cohort of the Born in Bradford birth cohort study. BMC Pregnancy Childbirth. 2014. 14:335 https://www.ncbi.nlm.nih.gov/pubmed/25261183 | Intervention/Exposure, Daily Eating Occasions Not Reported
743 | Petrella E, Facchinetti F, Bertarini V, Pignatti L, Neri I, Battistini NC. Occurrence of pregnancy complications in women with BMI >25 submitted to a healthy lifestyle and eating habits program. American journal of obstetrics and gynecology. 2013. 208:S33–S34 | Study Design, Publication Status
744 | Petrella E, Malavolti M, Bertarini V, Pignatti L, Neri I, Battistini NC, Facchinetti F. Gestational weight gain in overweight and obese women enrolled in a healthy lifestyle and eating habits program. J Matern Fetal Neonatal Med. 2014. 27:1348–52 https://www.ncbi.nlm.nih.gov/pubmed/24175912 | Intervention/Exposure, Daily Eating Occasions Not Reported
745 | Phelan S, Phipps MG, Abrams B, Darroch F, Schaffner A, Wing RR. Randomized trial of a behavioral intervention to prevent excessive gestational weight gain: the fit for delivery study. Obstetrical & gynecological survey. 2011. 66:471–472 | Study Design, Publication Status
746 | Phelan S, Wing RR, Brannen A, McHugh A, Hagobian TA, Schaffner A, Jelalian E, Hart CN, Scholl TO, Munoz-Christian K, Yin E, Phipps MG, Keadle S, Abrams B. Randomized controlled clinical trial of behavioral lifestyle intervention with partial meal replacement to reduce excessive gestational weight gain. Am J Clin Nutr. 2018. 107:183–194 https://www.ncbi.nlm.nih.gov/pubmed/29529157 | Intervention/Exposure, Daily Eating Occasions Not Reported
747 | Phelan S, Wyatt HR, Hill JO, Wing RR. Are the eating and exercise habits of successful weight losers changing?. Obesity (Silver Spring). 2006. 14:710–6 https://www.ncbi.nlm.nih.gov/pubmed/16741274 | Intervention/Exposure, Daily Eating Occasions Not Reported
748 | Pimenta AM, Bes-Rastrollo M, Gea A, Sayon-Orea C, Zazpe I, Lopez-Iracheta R, Martinez-Gonzalez MA. Snacking between main meals is associated with a higher risk of metabolic syndrome in a Mediterranean cohort: the SUN Project (Seguimiento Universidad de Navarra). Public Health Nutr. 2016. 19:658–66 https://www.ncbi.nlm.nih.gov/pubmed/25958949 | Daily Eating Occasions Not Reported
749 | Pincelli AI, Brunani A, Caumo A, Scacchi M, Pasqualinotto L, Tibaldi A, Dubini A, Bonadonna S, Cavagnini F. Hyperinsulinemia in the physiologic range is not superior to short-term fasting in suppressing insulin secretion in obese men. Metabolism. 2001. 50:107–11 https://www.ncbi.nlm.nih.gov/pubmed/11172483 | Intervention/Exposure, Daily Eating Occasions Not Reported, Size of Study Groups
750 | Pinto A, Bordoli C, Buckner L, Kaplan P, Arenal I, Jefcock E, Kim C, Johnston K, Hall W. A randomised controlled trial assessing the impact of intermittent energy restriction (IER) on weight loss and insulin sensitivity in healthy men and women with central obesity. the Met-IER study. Obesity facts. 2017. 10:157 | Publication Status
751 | Pinto AM, Bordoli C, Buckner LP, Kim C, Kaplan PC, Del Arenal IM, et al. Intermittent energy restriction is comparable to continuous energy restriction for cardiometabolic health in adults with central obesity: A randomized controlled trial; the Met-IER study. Clin Nutr. 2019. https://www.ncbi.nlm.nih.gov/pubmed/31409509. | Intervention/Exposure
752 | Pizinger T, Kovtun K, RoyChoudhury A, Laferrere B, Shechter A, St-Onge MP. Pilot study of sleep and meal timing effects, independent of sleep duration and food intake, on insulin sensitivity in healthy individuals. Sleep Health. 2018. 4:33–39 https://www.ncbi.nlm.nih.gov/pubmed/29332677 | Comparator, Size of Study Groups
753 | Plata-Salaman CR. Ingestive behavior and obesity. Nutrition. 2000. 16:797–9 https://www.ncbi.nlm.nih.gov/pubmed/11054583 | Study Design
754 | Ple. With a substantial breakfast to control hyperglycemia. MMW fortschritte der medizin. 2015;157 Suppl 1:9. https://www.ncbi.nlm.nih.gov/pubmed/26012964. | Language
755 | Poggiogalle E, Lubrano C, Gnessi L, Marocco C, Di Lazzaro L, Polidoro G, Luisi F, Merola G, Mariani S, Migliaccio S, Lenzi A, Donini LM. Reduced sleep duration affects body composition, dietary intake and quality of life in obese subjects. Eat Weight Disord. 2016. 21:501–505 https://www.ncbi.nlm.nih.gov/pubmed/26911383 | Intervention/Exposure
756 | Ponzo V, Gentile L, Gambino R, Rosato R, Cioffi I, Pellegrini N, Benso A, Broglio F, Cassader M, Bo S. Incidence of diabetes mellitus, cardiovascular outcomes and mortality after a 12-month lifestyle intervention: a 9-year follow-up. Diabetes & metabolism. 2018. 44:449–451 | Study Design, Publication Status
757 | Poston WS, Haddock CK, Pinkston MM, Pace P, Karakoc ND, Reeves RS, Foreyt JP. Weight loss with meal replacement and meal replacement plus snacks: a randomized trial. Int J Obes (Lond). 2005. 29:1107–14 https://www.ncbi.nlm.nih.gov/pubmed/15925955 | Intervention/Exposure
758 | Pot GK, Hardy R, Stephen AM. Irregular consumption of energy intake in meals is associated with a higher cardiometabolic risk in adults of a British birth cohort. Int J Obes (Lond). 2014. 38:1518–24 https://www.ncbi.nlm.nih.gov/pubmed/24675713 | Intervention/Exposure
759 | Pot GK, Hardy R, Stephen AM. Irregularity of energy intake at meals: prospective associations with the metabolic syndrome in adults of the 1946 British birth cohort. Br J Nutr. 2016. 115:315–23 https://www.ncbi.nlm.nih.gov/pubmed/26548599 | Intervention/Exposure, Comparator
760 | Ptomey LT, Steger FL, Schubert MM, Lee J, Willis EA, Sullivan DK, Szabo-Reed AN, Washburn RA, Donnelly JE. Breakfast Intake and Composition Is Associated with Superior Academic Achievement in Elementary Schoolchildren. J Am Coll Nutr. 2016. 35:326–33 https://www.ncbi.nlm.nih.gov/pubmed/26697955 | Study Design
761 | Purslow LR, Sandhu MS, Forouhi N, Young EH, Luben RN, Welch AA, Khaw K, Bingham SA, Wareham NJ. Energy intake at breakfast and weight change: prospective study of 6,764 middle-aged men and women. American journal of epidemiology. 2008;167(2):188–92. https://www.ncbi.nlm.nih.gov/pubmed/18079134. | Intervention/Exposure, Daily Eating Occasions Not Reported
762 | Quante M, Mariani S, Weng J, Marinac CR, Kaplan ER, Rueschman M, Mitchell JA, James P, Hipp JA, Cespedes Feliciano EM, Wang R, Redline S. Zeitgebers and their association with rest-activity patterns. Chronobiol Int. 2019. 36:203–213 https://www.ncbi.nlm.nih.gov/pubmed/30365354 | Study Design, Daily Eating Occasions Not Reported
763 | Quick V, Wall M, Larson N, Haines J, Neumark-Sztainer D. Personal, behavioral and socio-environmental predictors of overweight incidence in young adults: 10-yr longitudinal findings. Int J Behav Nutr Phys Act. 2013. 10:37 https://www.ncbi.nlm.nih.gov/pubmed/23531253 | Daily Eating Occasions Not Reported, Comparator
764 | Rabiee S, Afghari N, Rastmanesh R. Short-term and mid-term effects of fasting and downset meal pattern on lipid profile in Iranian fasted women. J Relig Health. 2014. 53:654–7 https://www.ncbi.nlm.nih.gov/pubmed/23111814 | Daily Eating Occasions Not Reported
765 | Racinais S, Periard JD, Li CK, Grantham J. Activity patterns, body composition and muscle function during Ramadan in a Middle-East Muslim country. Int J Sports Med. 2012. 33:641–6 https://www.ncbi.nlm.nih.gov/pubmed/22510804 | Daily Eating Occasions Not Reported
766 | Radhakishun N, Blokhuis C, van Vliet M, von Rosenstiel I, Weijer O, Heymans M, Beijnen J, Brandjes D, Diamant M. Intermittent fasting during Ramadan causes a transient increase in total, LDL, and HDL cholesterols and hs-CRP in ethnic obese adolescents. Eur J Pediatr. 2014. 173:1103–6 https://www.ncbi.nlm.nih.gov/pubmed/24522324 | Daily Eating Occasions Not Reported
767 | Raffoul A, Leatherdale ST, Kirkpatrick SI. Dieting predicts engagement in multiple risky behaviours among adolescent Canadian girls: a longitudinal analysis. Can J Public Health. 2018. 109:61–69 https://www.ncbi.nlm.nih.gov/pubmed/29981072 | Intervention/Exposure, Daily Eating Occasions Not Reported
768 | Rahbar AR, Safavi E, Rooholamini M, Jaafari F, Darvishi S, Rahbar A. Effects of Intermittent Fasting during Ramadan on Insulin-like Growth Factor-1, Interleukin 2, and Lipid Profile in Healthy Muslims. Int J Prev Med. 2019. 10:7 https://www.ncbi.nlm.nih.gov/pubmed/30774841 | Daily Eating Occasions Not Reported, Eating Frequency Data Collection
769 | Rakicioglu N, Samur G, Topcu A, Topcu AA. The effect of Ramadan on maternal nutrition and composition of breast milk. Pediatr Int. 2006. 48:278–83 https://www.ncbi.nlm.nih.gov/pubmed/16732795 | Outcome
770 | Ramadan J. Does fasting during Ramadan alter body composition, blood constituents and physical performance?. Med Princ Pract. 2002. 11 Suppl 2:41–6 https://www.ncbi.nlm.nih.gov/pubmed/12444309 | Intervention/Exposure, Daily Eating Occasions Not Reported
771 | Ramadan JM, Barac-Nieto M. Cardio-respiratory responses to moderately heavy aerobic exercise during the Ramadan fasts. Saudi Med J. 2000. 21:238–44 https://www.ncbi.nlm.nih.gov/pubmed/11533791 | Intervention/Exposure, Daily Eating Occasions Not Reported
772 | Ramiro-Gonzalez MD, Sanz-Barbero B, Royo-Bordonada MA. Childhood Excess Weight in Spain From 2006 to 2012. Determinants and Parental Misperception. Rev Esp Cardiol (Engl Ed). 2017. 70:656–663 https://www.ncbi.nlm.nih.gov/pubmed/28330819 | Study Design
773 | Ransom T, Goldenberg R, Mikalachki A, Prebtani APH, Punthakee Z. Reducing the Risk of Developing Diabetes. Canadian journal of diabetes. 2013;37(Suppl.1):S16–S9. https://www.ncbi.nlm.nih.gov/pubmed/24070941. | Study Design
774 | Rashidi MR, Mahboob S, Sattarivand R. Effects of nibbling and gorging on lipid profiles, blood glucose and insulin levels in healthy subjects. Saudi Med J. 2003. 24:945–8 https://www.ncbi.nlm.nih.gov/pubmed/12973474 | Country
775 | Rasmussen F, Kark M, Tholin S, Karnehed N, Tynelius P. The Swedish Young Male Twins Study: a resource for longitudinal research on risk factors for obesity and cardiovascular diseases. Twin Res Hum Genet. 2006. 9:883–9 https://www.ncbi.nlm.nih.gov/pubmed/17254425 | Study Design
776 | Ravussin E, Beyl RA, Poggiogalle E, Hsia DS, Peterson CM. Early Time-Restricted Feeding Reduces Appetite and Increases Fat Oxidation But Does Not Affect Energy Expenditure in Humans. Obesity (Silver Spring). 2019. 27:1244–1254 https://www.ncbi.nlm.nih.gov/pubmed/31339000 | Intervention/Exposure
777 | Reeves S, Huber JW, Halsey LG, Horabady-Farahani Y, Ijadi M, Smith T. Experimental manipulation of breakfast in normal and overweight/obese participants is associated with changes to nutrient and energy intake consumption patterns. Physiol Behav. 2014. 133:130–5 https://www.ncbi.nlm.nih.gov/pubmed/24866910 | Outcome
778 | Reeves S, Huber JW, Halsey LG, Villegas-Montes M, Elgumati J, Smith T. A cross-over experiment to investigate possible mechanisms for lower BMIs in people who habitually eat breakfast. Eur J Clin Nutr. 2015. 69:632–7 https://www.ncbi.nlm.nih.gov/pubmed/25563734 | Intervention/Exposure, Daily Eating Occasions Not Reported
779 | Reiches MW, Moore SE, Prentice AM, Ellison PT. Endocrine responses, weight change, and energy sparing mechanisms during Ramadan among Gambian adolescent women. Am J Hum Biol. 2014. 26:395–400 https://www.ncbi.nlm.nih.gov/pubmed/24590590 | Country
780 | Reid KJ, Baron KG, Zee PC. Meal timing influences daily caloric intake in healthy adults. Nutr Res. 2014. 34:930–5 https://www.ncbi.nlm.nih.gov/pubmed/25439026 | Study Design, Comparator
781 | Renault KM, Carlsen EM, Norgaard K, Nilas L, Pryds O, Secher NJ, Olsen SF, Halldorsson TI. Intake of Sweets, Snacks and Soft Drinks Predicts Weight Gain in Obese Pregnant Women: Detailed Analysis of the Results of a Randomised Controlled Trial. PLoS One. 2015. 10:e0133041 https://www.ncbi.nlm.nih.gov/pubmed/26192183 | Intervention/Exposure
782 | Rohin MA, Rozano N, Abd Hadi N, Mat Nor MN, Abdullah S, Dandinasivara Venkateshaiah M. Anthropometry and body composition status during Ramadan among higher institution learning centre staffs with different body weight status. ScientificWorldJournal. 2013. 2013:308041 https://www.ncbi.nlm.nih.gov/pubmed/24311975 | Intervention/Exposure, Daily Eating Occasions Not Reported
783 | Rong S, Snetselaar LG, Xu G, Sun Y, Liu B, Wallace RB, Bao W. Association of Skipping Breakfast With Cardiovascular and All-Cause Mortality. J Am Coll Cardiol. 2019. 73:2025–2032 https://www.ncbi.nlm.nih.gov/pubmed/31023424 | Eating Frequency Data Collection
784 | Rosbach S, Diederichs T, Bolzenius K, Buyken A, Alexy U. Age and time trends of circadian eating pattern in children and adolescents. Annals of nutrition and metabolism. Conference: 12^th^ european nutrition conference. 2015. 67:156 | Publication Status
785 | Rosi A, Martini D, Scazzina F, Dall’Aglio E, Leonardi R, Monti L, Fasano F, Di Dio C, Riggio L, Brighenti F. Nature and Cognitive Perception of 4 Different Breakfast Meals Influence Satiety-Related Sensations and Postprandial Metabolic Responses but Have Little Effect on Food Choices and Intake Later in the Day in a Randomized Crossover Trial in Healthy Men. J Nutr. 2018. 148:1536–1546 https://www.ncbi.nlm.nih.gov/pubmed/30204905 | Intervention/Exposure, Comparator
786 | Rosi A, Scazzina F, Brighenti F. Impact of different breakfast meals on food choices and eating behaviors. Annals of nutrition and metabolism. Conference: 12^th^ european nutrition conference. 2015. 67:133 https://doi.org/10.1159/000440895 | Publication Status
787 | Rothacker DQ, Staniszewski BA, Ellis PK. Liquid meal replacement vs traditional food: a potential model for women who cannot maintain eating habit change. J Am Diet Assoc. 2001. 101:345–7 https://www.ncbi.nlm.nih.gov/pubmed/11269616 | Intervention/Exposure, Daily Eating Occasions Not Reported, Comparator
788 | Ruge T, Svensson M, Eriksson JW, Olivecrona G. Tissue-specific regulation of lipoprotein lipase in humans: effects of fasting. Eur J Clin Invest. 2005. 35:194–200 https://www.ncbi.nlm.nih.gov/pubmed/15733074 | Intervention/Exposure
789 | Ruiz-Lozano T, Vidal J, de Hollanda A, Canteras M, Garaulet M, Izquierdo-Pulido M. Evening chronotype associates with obesity in severely obese subjects: interaction with CLOCK 3111T/C. Int J Obes (Lond). 2016. 40:1550–1557 https://www.ncbi.nlm.nih.gov/pubmed/27339606 | Health Status
790 | Saadatnia M, Zare M, Fatehi F, Ahmadi A. The effect of fasting on cerebral venous and dural sinus thrombosis. Neurol Res. 2009. 31:794–8 https://www.ncbi.nlm.nih.gov/pubmed/19723447 | Study Design, Daily Eating Occasions Not Reported
791 | Saarilehto S, Lapinleimu H, Keskinen S, Helenius H, Talvia S, Simell O. Growth, energy intake, and meal pattern in five-year-old children considered as poor eaters. J Pediatr. 2004. 144:363–7 https://www.ncbi.nlm.nih.gov/pubmed/15001944 | Intervention/Exposure, Daily Eating Occasions Not Reported
792 | Sadiya A, Ahmed S, Siddieg HH, Babas IJ, Carlsson M. Effect of Ramadan fasting on metabolic markers, body composition, and dietary intake in Emiratis of Ajman (UAE) with metabolic syndrome. Diabetes Metab Syndr Obes. 2011. 4:409–16 https://www.ncbi.nlm.nih.gov/pubmed/22253539 | Daily Eating Occasions Not Reported
793 | Safari K, Piro TJ, Ahmad HM. Perspectives and pregnancy outcomes of maternal Ramadan fasting in the second trimester of pregnancy. BMC Pregnancy Childbirth. 2019. 19:128 https://www.ncbi.nlm.nih.gov/pubmed/30987614 | Study Design
794 | Sakamaki R, Amamoto R, Mochida Y, Shinfuku N, Toyama K. A comparative study of food habits and body shape perception of university students in Japan and Korea. Nutr J. 2005. 4:31 https://www.ncbi.nlm.nih.gov/pubmed/16255785 | Study Design
795 | Sakar MN, Gultekin H, Demir B, Bakir VL, Balsak D, Vuruskan E, Acar H, Yucel O, Yayla M. Ramadan fasting and pregnancy: implications for fetal development in summer season. J Perinat Med. 2015. 43:319–23 https://www.ncbi.nlm.nih.gov/pubmed/24810552 | Outcome
796 | Sakurai M, Yoshita K, Nakamura K, Miura K, Takamura T, Nagasawa SY, Morikawa Y, Kido T, Naruse Y, Nogawa K, Suwazono Y, Sasaki S, Ishizaki M, Nakagawa H. Skipping breakfast and 5-year changes in body mass index and waist circumference in Japanese men and women. Obes Sci Pract. 2017. 3:162–170 https://www.ncbi.nlm.nih.gov/pubmed/28702211 | Daily Eating Occasions Not Reported
797 | Saleh SA, El-Kemery TA, Farrag KA, Badawy MR, Sarkis NN, Soliman FS, Mangoud H. Ramadan fasting: relation to atherogenic risk among obese Muslims. J Egypt Public Health Assoc. 2004. 79:461–83 https://www.ncbi.nlm.nih.gov/pubmed/17265611 | Daily Eating Occasions Not Reported
798 | Salehi M, Neghab M. Effects of fasting and a medium calorie balanced diet during the holy month Ramadan on weight, BMI and some blood parameters of overweight males. Pak J Biol Sci. 2007. 10:968–71 https://www.ncbi.nlm.nih.gov/pubmed/19069900 | Study Design, Comparator
799 | Samad F, Qazi F, Pervaiz MB, Kella DK, Mansoor M, Osmani BZ, Mir F, Kadir MM. Effects of ramadan fasting on blood pressure in normotensive males. J Ayub Med Coll Abbottabad. 2015. 27:338–42 https://www.ncbi.nlm.nih.gov/pubmed/26411111 | Intervention/Exposure, Daily Eating Occasions Not Reported
800 | Sandercock GR, Voss C, Dye L. Associations between habitual school-day breakfast consumption, body mass index, physical activity and cardiorespiratory fitness in English schoolchildren. Eur J Clin Nutr. 2010. 64:1086–92 https://www.ncbi.nlm.nih.gov/pubmed/20683459 | Study Design
801 | Sandhu SK, Tang TS. Whens dinner? Does timing of dinner affect the cardiometabolic risk profiles of South-Asian Canadians at risk for diabetes. Diabet Med. 2017. 34:539–542 https://www.ncbi.nlm.nih.gov/pubmed/26802477 | Study Design
802 | Sarraf-Zadegan N, Atashi M, Naderi GA, Baghai AM, Asgary S, Fatehifar MR, Samarian H, Zarei M. The effect of fasting in Ramadan on the values and interrelations between biochemical, coagulation and hematological factors. Ann Saudi Med. 2000. 20:377–81 https://www.ncbi.nlm.nih.gov/pubmed/17264626 | Daily Eating Occasions Not Reported
803 | Sarri KO, Linardakis MK, Bervanaki FN, Tzanakis NE, Kafatos AG. Greek Orthodox fasting rituals: a hidden characteristic of the Mediterranean diet of Crete. Br J Nutr. 2004. 92:277–84 https://www.ncbi.nlm.nih.gov/pubmed/15333159 | Intervention/Exposure, Daily Eating Occasions Not Reported
804 | Sarri KO, Tzanakis NE, Linardakis MK, Mamalakis GD, Kafatos AG. Effects of Greek Orthodox Christian Church fasting on serum lipids and obesity. BMC Public Health. 2003. 3:16 https://www.ncbi.nlm.nih.gov/pubmed/12753698 | Intervention/Exposure, Daily Eating Occasions Not Reported
805 | Sasaki S, Nakae S, Ebine N, Aoi W, Higashi A, Ishii K. The effect of the timing of meal intake on energy metabolism during moderate exercise. J Nutr Sci Vitaminol (Tokyo). 2014. 60:28–34 https://www.ncbi.nlm.nih.gov/pubmed/24759257 | Intervention/Exposure, Daily Eating Occasions Not Reported, Size of Study Groups
806 | Sassi M, Chakroun T, Chouchene S, Hellara I, Boubaker H, Grissa MH, Khochtali I, Hassine M, Addad F, Elalamy I, Nouira S. Does Lipid Profile Affect Thrombin Generation During Ramadan Fasting in Patients With Cardiovascular Risks?. Clin Appl Thromb Hemost. 2017. 23:980–986 https://www.ncbi.nlm.nih.gov/pubmed/27613563 | Study Design, Daily Eating Occasions Not Reported
807 | Sata M, Yamagishi K, Sairenchi T, Ikeda A, Irie F, Watanabe H, Iso H, Ota H. Impact of Caregiver Type for 3-YearOld Children on Subsequent Between-Meal Eating Habits and Being Overweight From Childhood to Adulthood: A 20-Year Follow-up of the Ibaraki Childrens Cohort (IBACHIL) Study. J Epidemiol. 2015. 25:600–7 https://www.ncbi.nlm.nih.gov/pubmed/26310570 | Daily Eating Occasions Not Reported, Comparator
808 | Sato M, Nakamura K, Ogata H, Miyashita A, Nagasaka S, Omi N, Yamaguchi S, Hibi M, Umeda T, Nakaji S, Tokuyama K. Acute effect of late evening meal on diurnal variation of blood glucose and energy metabolism. Obes Res Clin Pract. 2011. 5:e169–266 https://www.ncbi.nlm.nih.gov/pubmed/24331104 | Intervention/Exposure, Comparator
809 | Savitri AI, Yadegari N, Bakker J, van Ewijk RJ, Grobbee DE, Painter RC, Uiterwaal CS, Roseboom TJ. Ramadan fasting and newborns birth weight in pregnant Muslim women in The Netherlands. Br J Nutr. 2014. 112:1503–9 https://www.ncbi.nlm.nih.gov/pubmed/25231606 | Intervention/Exposure, Daily Eating Occasions Not Reported, Outcome
810 | Sayn-Orea C, Bes-Rastrollo M, Carlos S, Beunza JJ, Basterra-Gortari FJ, Martnez-Gonzlez MA. Association between sleeping hours and siesta and the risk of obesity: The SUN mediterranean cohort. Obesity facts. 2013;6(4):337–47. https://www.ncbi.nlm.nih.gov/pubmed/23970143. | Intervention/Exposure
811 | Schlogl M, Piaggi P, Pannacciuli N, Bonfiglio SM, Krakoff J, Thearle MS. Energy Expenditure Responses to Fasting and Overfeeding Identify Phenotypes Associated With Weight Change. Diabetes. 2015. 64:3680–9 https://www.ncbi.nlm.nih.gov/pubmed/26185280 | Intervention/Exposure, Daily Eating Occasions Not Reported
812 | Schnepper R, Richard A, Wilhelm FH, Blechert J. A combined mindfulness-prolonged chewing intervention reduces body weight, food craving, and emotional eating. J Consult Clin Psychol. 2019. 87:106–111 https://www.ncbi.nlm.nih.gov/pubmed/30570305 | Intervention/Exposure
813 | Schuz B, Schuz N, Ferguson SG. It’s the power of food: individual differences in food cue responsiveness and snacking in everyday life. Int J Behav Nutr Phys Act. 2015. 12:149 https://www.ncbi.nlm.nih.gov/pubmed/26643690 | Intervention/Exposure, Daily Eating Occasions Not Reported, Outcome
814 | Schyns G, van den Akker K, Roefs A, Houben K, Jansen A. Exposure therapy vs lifestyle intervention to reduce food cue reactivity and binge eating in obesity: A pilot study. J Behav Ther Exp Psychiatry. 2019. https://www.ncbi.nlm.nih.gov/pubmed/30732912. | Intervention/Exposure, Size of Study Groups
815 | Seal N. Eating patterns of family with overweight preschool children. Communicating Nursing Research. 2007. 40:505–505 | Intervention/Exposure, Publication Status
816 | Seker A, Demirci H, Ocakoglu G, Aydin U, Ucar H, Yildiz G, Yaman O. Effect of fasting on 24-h blood pressure values of individuals with no previous history of hypertension. Blood Press Monit. 2017. 22:247–252 https://www.ncbi.nlm.nih.gov/pubmed/28225380 | Daily Eating Occasions Not Reported
817 | Sezen Y, Altiparmak IH, Erkus ME, Kocarslan A, Kaya Z, Gunebakmaz O, Demirbag R. Effects of Ramadan fasting on body composition and arterial stiffness. J Pak Med Assoc. 2016. 66:1522–1527 https://www.ncbi.nlm.nih.gov/pubmed/27924959 | Intervention/Exposure, Daily Eating Occasions Not Reported
818 | Shariatpanahi MV, Shariatpanahi ZV, Shahbazi S, Moshtaqi M. Effect of fasting with two meals on BMI and inflammatory markers of metabolic syndrome. Pak J Biol Sci. 2012. 15:255–8 https://www.ncbi.nlm.nih.gov/pubmed/24199461 | Daily Eating Occasions Not Reported, Comparator
819 | Shariatpanahi ZV, Shariatpanahi MV, Shahbazi S, Hossaini A, Abadi A. Effect of Ramadan fasting on some indices of insulin resistance and components of the metabolic syndrome in healthy male adults. Br J Nutr. 2008. 100:147–51 https://www.ncbi.nlm.nih.gov/pubmed/18053308 | Outcome
820 | Shashaj B, Graziani MP, Contoli B, Ciuffo C, Cives C, Facciolini S, Rigoni ML, Spaterna S, Taucci M, Raponi M, Manco M. Energy Balance-Related Behaviors, Perinatal, Sociodemographic, and Parental Risk Factors Associated with Obesity in Italian Preschoolers. J Am Coll Nutr. 2016. 35:362–71 https://www.ncbi.nlm.nih.gov/pubmed/26933953 | Study Design
821 | Shehab A, Abdulle A, El Issa A, Al Suwaidi J, Nagelkerke N. Favorable changes in lipid profile: the effects of fasting after Ramadan. PLoS One. 2012. 7:e47615 https://www.ncbi.nlm.nih.gov/pubmed/23112824 | Daily Eating Occasions Not Reported
822 | Shim E, Ryu HJ, Hwang J, Kim SY, Chung EJ. Dietary sodium intake in young Korean adults and its relationship with eating frequency and taste preference. Nutr Res Pract. 2013. 7:192–8 https://www.ncbi.nlm.nih.gov/pubmed/23766880 | Study Design, Intervention/Exposure, Outcome
823 | Shirreffs SM, Maughan RJ. Water and salt balance in young male football players in training during the holy month of Ramadan. J Sports Sci. 2008. 26 Suppl 3:S47–54 https://www.ncbi.nlm.nih.gov/pubmed/19085452 | Intervention/Exposure, Daily Eating Occasions Not Reported
824 | Shisslak CM, Mays MZ, Crago M, Jirsak JK, Taitano K, Cagno C. Eating and weight control behaviors among middle school girls in relationship to body weight and ethnicity. J Adolesc Health. 2006. 38:631–3 https://www.ncbi.nlm.nih.gov/pubmed/16635783 | Study Design, Intervention/Exposure
825 | Short R. Matters of the heart. Nurs Older People. 2006. 18:16–8 https://www.ncbi.nlm.nih.gov/pubmed/17260594 | Study Design
826 | Shroff MR, Perng W, Baylin A, Mora-Plazas M, Marin C, Villamor E. Adherence to a snacking dietary pattern and soda intake are related to the development of adiposity: a prospective study in school-age children. Public Health Nutr. 2014. 17:1507–13 https://www.ncbi.nlm.nih.gov/pubmed/23701749 | Intervention/Exposure
827 | Siega-Riz AM, Herrmann TS, Savitz DA, Thorp JM. Frequency of eating during pregnancy and its effect on preterm delivery. American journal of epidemiology. 2001;153(7):647–52. https://www.ncbi.nlm.nih.gov/pubmed/11282791. | Outcome
828 | Siegel AJ, Bhatti NA, Wasfy JH. Reprising Ramadan-Related Angina Pectoris: A Potential Strategy for Risk Reduction. Am J Case Rep. 2016. 17:841–844 https://www.ncbi.nlm.nih.gov/pubmed/27829657 | Study Design
829 | Siklova M, Krauzova E, Svobodova B, Kracmerova J, Stepan M, Koc M, Stich V, Rossmeislova L. Circulating Monocyte and Lymphocyte Populations in Healthy First-Degree Relatives of Type 2 Diabetic Patients at Fasting and during Short-Term Hyperinsulinemia. Mediators Inflamm. 2019. 2019:1491083 https://www.ncbi.nlm.nih.gov/pubmed/30983877 | Intervention/Exposure
830 | Simmons D, Jelsma JG, Galjaard S, Devlieger R, van Assche A, Jans G, Corcoy R, Adelantado JM, Dunne F, Desoye G, Harreiter J, Kautzky-Willer A, Damm P, Mathiesen ER, Jensen DM, Andersen LL, Lapolla A, Dalfra M, Bertolotto A, Wender-Ozegowska E, Zawiejska A, Hill D, Rebollo P, Snoek FJ, van Poppel MN. Results From a European Multicenter Randomized Trial of Physical Activity and/or Healthy Eating to Reduce the Risk of Gestational Diabetes Mellitus: The DALI Lifestyle Pilot. Diabetes Care. 2015. 38:1650–6 https://www.ncbi.nlm.nih.gov/pubmed/26112044 | Intervention/Exposure
831 | Singh RB, Takahashi T, Hristova K, Maheshwari A, Niaz MA, De Meester F, Saboo B, Elkilany G, Srivastav SSL, Srivastav V, etal. Effects of circadian-restricted feeding and low energy intake, on risk of cardiovascular disease and type 2 diabetes mellitus. World heart journal. 2016. 8:315–327 | Daily Eating Occasions Not Reported
832 | Sirbu E, Buzas R, Mihaescu R, Suceava I, Lighezan D. Influence of exercise training and eating behavior on arterial stiffness in young healthy students. Wien Klin Wochenschr. 2015. 127:555–60 https://www.ncbi.nlm.nih.gov/pubmed/26033407 | Daily Eating Occasions Not Reported, Comparator
833 | Siu PMF, Wong SHS, Morris WJ, Chung S. Influence of feeding pattern on postprandial blood glucose responses. Hong Kong Journal of Sports Medicine & Sports Science. 2001. 13:52–55 | Daily Eating Occasions Not Reported
834 | Skipping meals might increase the risk of metabolic syndrome. Nature Clinical Practice Endocrinology and Metabolism. 2008. 4:532–533 | Publication Status
835 | Skogheim TS, Vollrath ME. Associations of Child Temperament with Child Overweight and Breakfast Habits: A Population Study in Five-Year-Olds. Nutrients. 2015. 7:10116–28 https://www.ncbi.nlm.nih.gov/pubmed/26633494 | Study Design
836 | St-Onge MP, Pizinger T, Kovtun K, RoyChoudhury A. Sleep and meal timing influence food intake and its hormonal regulation in healthy adults with overweight/obesity. Eur J Clin Nutr. 2019;72(Suppl 1):76–82. https://www.ncbi.nlm.nih.gov/pubmed/30487565. | Comparator
837 | Smeets AJ, Westerterp-Plantenga MS. Acute effects on metabolism and appetite profile of one meal difference in the lower range of meal frequency. Br J Nutr. 2008. 99:1316–21 https://www.ncbi.nlm.nih.gov/pubmed/18053311 | Outcome
838 | Smith C, Richards R. Dietary intake, overweight status, and perceptions of food insecurity among homeless Minnesotan youth. Am J Hum Biol. 2008. 20:550–63 https://www.ncbi.nlm.nih.gov/pubmed/18491407 | Study Design
839 | Smith DM, Taylor W, Lavender T. Behaviour change techniques to change the postnatal eating and physical activity behaviours of women who are obese: a qualitative study. Bjog. 2016. 123:279–84 https://www.ncbi.nlm.nih.gov/pubmed/26537206 | Study Design
840 | Smith KJ, Gall SL, McNaughton SA, Blizzard L, Dwyer T, Venn AJ. Skipping breakfast: longitudinal associations with cardiometabolic risk factors in the Childhood Determinants of Adult Health Study. Am J Clin Nutr. 2010. 92:1316–25 https://www.ncbi.nlm.nih.gov/pubmed/20926520 | Daily Eating Occasions Not Reported
841 | Smith KL, Straker LM, Kerr DA, Smith AJ. Overweight adolescents eat what? And when? Analysis of consumption patterns to guide dietary message development for intervention. J Hum Nutr Diet. 2015. 28 Suppl 2:80–93 https://www.ncbi.nlm.nih.gov/pubmed/25157498 | Study Design, Intervention/Exposure, Daily Eating Occasions Not Reported, Outcome
842 | Smith TJ, Dotson LE, Young AJ, White A, Hadden L, Bathalon GP, Funderburk L, Marriott BP. Eating patterns and leisure-time exercise among active duty military personnel: comparison to the Healthy People objectives. J Acad Nutr Diet. 2013. 113:907–19 https://www.ncbi.nlm.nih.gov/pubmed/23647834 | Study Design
843 | Snoek HM, van Strien T, Janssens JM, Engels RC. Emotional, external, restrained eating and overweight in Dutch adolescents. Scand J Psychol. 2007. 48:23–32 https://www.ncbi.nlm.nih.gov/pubmed/17257366 | Study Design
844 | So HK, Nelson EAS, Li AM, Guldan GS, Yin J, Ng PC, et al. Breakfast frequency inversely associated with BMI and body fatness in Hong Kong Chinese children aged 9-18 years. British journal of nutrition. 2011;106(5):742–51. https://www.ncbi.nlm.nih.gov/pubmed/21535905. | Study Design
845 | Soeters MR, Lammers NM, Dubbelhuis PF, Ackermans M, Jonkers-Schuitema CF, Fliers E, Sauerwein HP, Aerts JM, Serlie MJ. Intermittent fasting does not affect whole-body glucose, lipid, or protein metabolism. Am J Clin Nutr. 2009. 90:1244–51 https://www.ncbi.nlm.nih.gov/pubmed/19776143 | Daily Eating Occasions Not Reported
846 | Sok SR, Kim OS, Park MH. Effects of Obesity Management Program Provided by Occupational Health Nurse in Worksite. West J Nurs Res. 2019. 41:728–742 https://www.ncbi.nlm.nih.gov/pubmed/30541407 | Intervention/Exposure
847 | Solah VA, Kerr DA, Hunt WJ, Johnson SK, Boushey CJ, Delp EJ, et al. Effect of Fibre Supplementation on Body Weight and Composition, Frequency of Eating and Dietary Choice in Overweight Individuals. Nutrients. 2017;9(2). https://www.ncbi.nlm.nih.gov/pubmed/28212353. | Intervention/Exposure
848 | Solianik R, Sujeta A. Two-day fasting evokes stress, but does not affect mood, brain activity, cognitive, psychomotor, and motor performance in overweight women. Behav Brain Res. 2018. 338:166–172 https://www.ncbi.nlm.nih.gov/pubmed/29097329 | Daily Eating Occasions Not Reported
849 | Soreca I, Wallace ML, Hall MH, Hasler BP, Frank E, Kupfer DJ. The association between meal timing and frequency with cardiometabolic profile in patients with bipolar disorder. Acta Psychiatr Scand. 2016. 133:453–8 https://www.ncbi.nlm.nih.gov/pubmed/27084394 | Study Design, Health Status
850 | Souissi N, Souissi H, Sahli S, Tabka Z, Dogui M, Ati J, Davenne D. Effect of Ramadan on the diurnal variation in short-term high power output. Chronobiol Int. 2007. 24:991–1007 https://www.ncbi.nlm.nih.gov/pubmed/17994351 | Intervention/Exposure, Daily Eating Occasions Not Reported, Outcome
851 | Spaeth AM, Dinges DF, Goel N. Effects of Experimental Sleep Restriction on Weight Gain, Caloric Intake, and Meal Timing in Healthy Adults. Sleep. 2013. 36:981–990 https://www.ncbi.nlm.nih.gov/pubmed/23814334 | Intervention/Exposure, Outcome
852 | Spaeth AM, Dinges DF, Goel N. Sex and race differences in caloric intake during sleep restriction in healthy adults. Am J Clin Nutr. 2014. 100:559–66 https://www.ncbi.nlm.nih.gov/pubmed/24965304 | Daily Eating Occasions Not Reported
853 | Spaeth AM, Hawley NL, Raynor HA, Jelalian E, Greer A, Crouter SE, Coffman DL, Carskadon MA, Owens JA, Wing RR, Hart CN. Sleep, energy balance, and meal timing in school-aged children. Sleep Med. 2019. 60:139–144 https://www.ncbi.nlm.nih.gov/pubmed/30905623 | Study Design
854 | Sriha Belguith A, Baccouche H, Grissa MH, Boubaker H, Bouida W, Beltaief K, Sekma A, Fredj N, Bzeouiche N, Zina Z, Boukef R, Soltani M, Nouira S. The risk of acute coronary syndrome in Ramadan. Tunis Med. 2016. 94:599–603 https://www.ncbi.nlm.nih.gov/pubmed/28972251 | Language
855 | Stange R, Pflugbeil C, Michalsen A, Uehleke B. Therapeutic fasting in patients with metabolic syndrome and impaired insulin resistance. Forsch Komplementmed. 2013. 20:421–6 https://www.ncbi.nlm.nih.gov/pubmed/24434756 | Intervention/Exposure, Daily Eating Occasions Not Reported
856 | Stannard SR, Thompson MW, Fairbairn K, Huard B, Sachinwalla T, Thompson CH. Fasting for 72 h increases intramyocellular lipid content in nondiabetic, physically fit men. Am J Physiol Endocrinol Metab. 2002. 283:E1185–91 https://www.ncbi.nlm.nih.gov/pubmed/12388154 | Intervention/Exposure, Daily Eating Occasions Not Reported, Size of Study Groups
857 | Stannard SR, Thompson MW. The effect of participation in Ramadan on substrate selection during submaximal cycling exercise. J Sci Med Sport. 2008. 11:510–7 https://www.ncbi.nlm.nih.gov/pubmed/17706462 | Intervention/Exposure, Daily Eating Occasions Not Reported
858 | Stea TH, Vik FN, Bere E, Svendsen MV, Oellingrath IM. Meal pattern among Norwegian primary-school children and longitudinal associations between meal skipping and weight status. Public Health Nutr. 2015. 18:286–91 https://www.ncbi.nlm.nih.gov/pubmed/24521714 | Daily Eating Occasions Not Reported
859 | Stekovic S, Hofer SJ, Tripolt N, Aon MA, Royer P, Pein L, Stadler JT, Pendl T, Prietl B, Url J, Schroeder S, Tadic J, Eisenberg T, Magnes C, Stumpe M, Zuegner E, Bordag N, Riedl R, Schmidt A, Kolesnik E, Verheyen N, Springer A, Madl T, Sinner F, de Cabo R, Kroemer G, Obermayer-Pietsch B, Dengjel J, Sourij H, Pieber TR, Madeo F. Alternate Day Fasting Improves Physiological and Molecular Markers of Aging in Healthy, Non-obese Humans. Cell Metab. 2019. 30:462–476.e5 https://www.ncbi.nlm.nih.gov/pubmed/31471173 | Intervention/Exposure, Daily Eating Occasions Not Reported
860 | Stote KS, Baer DJ, Spears K, Paul DR, Harris GK, Rumpler WV, Strycula P, Najjar SS, Ferrucci L, Ingram DK, Longo DL, Mattson MP. A controlled trial of reduced meal frequency without caloric restriction in healthy, normalweight, middle-aged adults. Am J Clin Nutr. 2007. 85:981–8 https://www.ncbi.nlm.nih.gov/pubmed/17413096 | Eating Frequency Data Collection
861 | Striegel-Moore RH, Rosselli F, Wilson GT, Perrin N, Harvey K, DeBar L. Nocturnal eating: association with binge eating, obesity, and psychological distress. Int J Eat Disord. 2010. 43:520–6 https://www.ncbi.nlm.nih.gov/pubmed/19708071 | Daily Eating Occasions Not Reported
862 | Stroebele N, McNally J, Plog A, Siegfried S, Hill JO. The association of self-reported sleep, weight status, and academic performance in fifth-grade students. J Sch Health. 2013. 83:77–84 https://www.ncbi.nlm.nih.gov/pubmed/23331266 | Study Design
863 | Sudharsanan N, Romano S, Cunningham SA. School Breakfast Receipt and Obesity among American Fifth- and Eighth-Graders. J Acad Nutr Diet. 2016. 116:599–607.e3 https://www.ncbi.nlm.nih.gov/pubmed/27046061 | Intervention/Exposure, Daily Eating Occasions Not Reported
864 | Sugimori H, Yoshida K, Izuno T, Miyakawa M, Suka M, Sekine M, Yamagami T, Kagamimori S. Analysis of factors that influence body mass index from ages 3 to 6 years: A study based on the Toyama cohort study. Pediatr Int. 2004. 46:302–10 https://www.ncbi.nlm.nih.gov/pubmed/15151547 | Intervention/Exposure, Daily Eating Occasions Not Reported
865 | Sülü B, Öztürk B, Güven A, Kiliç K. The effect of long-term controlled fasting (the Ramadan model) on body mass index, blood biochemistry and oxidative stress factors. Turkiye Klinikleri Journal of Medical Sciences. 2010. 30:855–863 http://search.ebscohost.com/login.aspx?direct=true&db=jlh&AN=105091038&site=ehost-live | Daily Eating Occasions Not Reported
866 | Sundfor TM, Svendsen M, Tonstad S. Effect of intermittent versus continuous energy restriction on weight loss, maintenance and cardiometabolic risk: A randomized 1-year trial. Nutr Metab Cardiovasc Dis. 2018. 28:698–706 https://www.ncbi.nlm.nih.gov/pubmed/29778565 | Daily Eating Occasions Not Reported
867 | Sundfor TM, Tonstad S, Svendsen M. Effects of intermittent versus continuous energy restriction for weight loss on diet quality and eating behavior. A randomized trial. Eur J Clin Nutr. 2019. 73:1006–1014 https://www.ncbi.nlm.nih.gov/pubmed/30514879 | Daily Eating Occasions Not Reported
868 | Supak-Smolcic V, Antoncic D, Ozanic D, Vladilo I, Bilic-Zulle L. Influence of a prolonged fasting and mild activity on routine laboratory tests. Clin Biochem. 2015. 48:85–8 https://www.ncbi.nlm.nih.gov/pubmed/25445731 | Study Design, Daily Eating Occasions Not Reported, Comparator
869 | Suriani I, Shamsuddin K, Abdul Latif K, Saad HA. The effect of the Malaysian Food Guideline guidance on a group of overweight and obese women during Ramadan. Saudi Med J. 2015. 36:40–5 https://www.ncbi.nlm.nih.gov/pubmed/25630003 | Intervention/Exposure, Daily Eating Occasions Not Reported
870 | Sutton EF, Beyl R, Early KS, Cefalu WT, Ravussin E, Peterson CM. Early Time-Restricted Feeding Improves Insulin Sensitivity, Blood Pressure, and Oxidative Stress Even without Weight Loss in Men with Prediabetes. Cell Metab. 2018. 27:1212–1221.e3 https://www.ncbi.nlm.nih.gov/pubmed/29754952 | Daily Eating Occasions Not Reported
871 | Syam AF. Fasting Can Prevent Various Chronic Diseases. Acta Med Indones. 2016. 48:167–168 https://www.ncbi.nlm.nih.gov/pubmed/27847381 | Study Design, Publication Status
872 | Syrad H, Llewellyn CH, Johnson L, Boniface D, Jebb SA, van Jaarsveld CH, Wardle J. Meal size is a critical driver of weight gain in early childhood. Sci Rep. 2016. 6:28368 https://www.ncbi.nlm.nih.gov/pubmed/27321917 | Age: Intervention/Exposure
873 | Taillie LS, Wang D, Popkin BM. Snacking Is Longitudinally Associated with Declines in Body Mass Index z Scores for Overweight Children, but Increases for Underweight Children. J Nutr. 2016. 146:1268–75 https://www.ncbi.nlm.nih.gov/pubmed/27146917 | Daily Eating Occasions Not Reported
874 | Talib RA, Canguven O, Al-Rumaihi K, Al Ansari A, Alani M. The effect of fasting on erectile function and sexual desire on men in the month of Ramadan. Urol J. 2015. 12:2099–102 https://www.ncbi.nlm.nih.gov/pubmed/25923156 | Intervention/Exposure, Daily Eating Occasions Not Reported
875 | Tambalis KD, Panagiotakos DB, Psarra G, Sidossis LS. Association of cardiorespiratory fitness levels with dietary habits and lifestyle factors in schoolchildren. Appl Physiol Nutr Metab. 2019. 44:539–545 https://www.ncbi.nlm.nih.gov/pubmed/30321490 | Study Design, Intervention/Exposure
876 | Tan CC, Walczak M, Roach E, Lumeng JC, Miller AL. Longitudinal associations between eating and drinking engagement during mealtime and eating in the absence of hunger in low income toddlers. Appetite. 2018. 130:29–34 https://www.ncbi.nlm.nih.gov/pubmed/30059768 | Intervention/Exposure
877 | Taveras EM, Rifas-Shiman SL, Berkey CS, Rockett HR, Field AE, Frazier AL, et al. Family dinner and adolescent overweight. Obesity research. 2005;13(5):900–6. https://www.ncbi.nlm.nih.gov/pubmed/15919844. | Intervention/Exposure, Daily Eating Occasions Not Reported
878 | Taylor MA, Garrow JS. Compared with nibbling, neither gorging nor a morning fast affect short-term energy balance in obese patients in a chamber calorimeter. Int J Obes Relat Metab Disord. 2001. 25:519–28 https://www.ncbi.nlm.nih.gov/pubmed/11319656 | Outcome
879 | Taylor RW, Iosua E, Heath AM, Gray AR, Taylor BJ, Lawrence JA, Hanna M, Cameron SL, Sayers R, Galland B. Eating frequency in relation to BMI in very young children: a longitudinal analysis. Public Health Nutr. 2017. 20:1372–1379 https://www.ncbi.nlm.nih.gov/pubmed/28238299 | Eating Frequency Data Collection
880 | Teixeira GP, Barreto ACF, Mota MC, Crispim CA. Caloric midpoint is associated with total calorie and macronutrient intake and body mass index in undergraduate students. Chronobiol Int. 2019. 36:1418–1428 https://www.ncbi.nlm.nih.gov/pubmed/31409139 | Study Design, Intervention/Exposure, Outcome
881 | Teixeira GP, Mota MC, Crispim CA. Eveningness is associated with skipping breakfast and poor nutritional intake in Brazilian undergraduate students. Chronobiol Int. 2018. 35:358–367 https://www.ncbi.nlm.nih.gov/pubmed/29219626 | Study Design, Outcome
882 | Teixeira PD, Reis BZ, Vieira DA, Costa D, Costa JO, Raposo OF, et al. Educational nutritional intervention as an effective tool for changing eating habits and body weight among those who practice physical activities. Ciencia & saude coletiva. 2013;18(2):347–56. https://www.ncbi.nlm.nih.gov/pubmed/23358760. | Language
883 | Tejpal S, Sanghera N, Manoharan V, Planas-Iglesias J, Myler K, Klein-Seetharaman J. Towards personalised molecular feedback for weight loss. BMC Obes. 2019. 6:20 https://www.ncbi.nlm.nih.gov/pubmed/31080628 | Daily Eating Occasions Not Reported, Comparator
884 | Teng NI, Shahar S, Manaf ZA, Das SK, Taha CS, Ngah WZ. Efficacy of fasting calorie restriction on quality of life among aging men. Physiol Behav. 2011. 104:1059–64 https://www.ncbi.nlm.nih.gov/pubmed/21781980 | Intervention/Exposure, Daily Eating Occasions Not Reported
885 | Thankamony A, Capalbo D, Marcovecchio ML, Sleigh A, Jorgensen SW, Hill NR, Mooslehner K, Yeo GS, Bluck L, Juul A, Vaag A, Dunger DB. Low circulating levels of IGF-1 in healthy adults are associated with reduced beta-cell function, increased intramyocellular lipid, and enhanced fat utilization during fasting. J Clin Endocrinol Metab. 2014. 99:2198–207 https://www.ncbi.nlm.nih.gov/pubmed/24617714 | Intervention/Exposure, Daily Eating Occasions Not Reported
886 | Thiara B. Cardiovascular disease. Nurs Stand. 2015. 29:60 https://www.ncbi.nlm.nih.gov/pubmed/25872853 | Study Design, Intervention/Exposure
887 | Thivel D, Finlayson G, Miguet M, Pereira B, Duclos M, Boirie Y, Doucet E, Blundell JE, Metz L. Energy depletion by 24-h fast leads to compensatory appetite responses compared with matched energy depletion by exercise in healthy young males. Br J Nutr. 2018. 120:583–592 https://www.ncbi.nlm.nih.gov/pubmed/30058508 | Daily Eating Occasions Not Reported, Size of Study Groups
888 | Thomas EA, Higgins J, Bessesen DH, McNair B, Cornier MA. Usual breakfast eating habits affect response to breakfast skipping in overweight women. Obesity. 2015. 23:750–9 https://www.ncbi.nlm.nih.gov/pubmed/25755093 | Daily Eating Occasions Not Reported
889 | Timlin MT, Pereira MA, Story M, Neumark-Sztainer D. Breakfast eating and weight change in a 5-year prospective analysis of adolescents: Project EAT (Eating Among Teens). Pediatrics. 2008. 121:e638–45 https://www.ncbi.nlm.nih.gov/pubmed/18310183 | Daily Eating Occasions Not Reported
890 | Timlin MT, Pereira MA. Breakfast frequency and quality in the etiology of adult obesity and chronic diseases. Nutrition reviews. 2007;65(6):268–81. https://www.ncbi.nlm.nih.gov/pubmed/17605303. | Study Design
891 | Timmermans M, Mackenbach JD, Charreire H, Bardos H, Compernolle S, De Bourdeaudhuij I, Oppert JM, Rutter H, McKee M, Lakerveld J. Exploring the mediating role of energy balance-related behaviours in the association between sleep duration and obesity in European adults. The SPOTLIGHT project. Prev Med. 2017. 100:25–32 https://www.ncbi.nlm.nih.gov/pubmed/28359703 | Study Design, Daily Eating Occasions Not Reported
892 | Tin SP, Ho SY, Mak KH, Wan KL, Lam TH. Breakfast skipping and change in body mass index in young children. Int J Obes. 2011. 35:899–906 https://www.ncbi.nlm.nih.gov/pubmed/21448130 | Daily Eating Occasions Not Reported
893 | Tin SP, Ho SY, Mak KH, Wan KL, Lam TH. Lifestyle and socioeconomic correlates of breakfast skipping in Hong Kong primary 4 schoolchildren. Prev Med. 2011. 52:250–3 https://www.ncbi.nlm.nih.gov/pubmed/21215276 | Study Design
894 | Tin SP, Ho SY, Mak KH, Wan KL, Lam TH. Location of breakfast consumption predicts body mass index change in young Hong Kong children. Int J Obes. 2012. 36:925–30 https://www.ncbi.nlm.nih.gov/pubmed/22234278 | Intervention/Exposure
895 | Tinsley GM, Forsse JS, Butler NK, Paoli A, Bane AA, La Bounty PM, Morgan GB, Grandjean PW. Time-restricted feeding in young men performing resistance training: A randomized controlled trial. Eur J Sport Sci. 2017. 17:200–207 https://www.ncbi.nlm.nih.gov/pubmed/27550719 | Daily Eating Occasions Not Reported
896 | Tinsley GM, Moore ML, Graybeal AJ, Paoli A, Kim Y, Gonzales JU, Harry JR, VanDusseldorp TA, Kennedy DN, Cruz MR. Time-restricted feeding plus resistance training in active females: a randomized trial. Am J Clin Nutr. 2019. 110:628–640 https://www.ncbi.nlm.nih.gov/pubmed/31268131 | Intervention/Exposure
897 | Tinsley GM, Moore ML, Graybeal AJ. Reliability of hunger-related assessments during 24-hour fasts and their relationship to body composition and subsequent energy compensation. Physiol Behav. 2018. 188:221–226 https://www.ncbi.nlm.nih.gov/pubmed/29438660 | Daily Eating Occasions Not Reported, Size of Study Groups
898 | Topacoglu H, Karcioglu O, Yuruktumen A, Kiran S, Cimrin AH, Ozucelik DN, Sarikaya S, Soysal S, Turpcu U, Bozkurt S. Impact of Ramadan on demographics and frequencies of disease-related visits in the emergency department. Int J Clin Pract. 2005. 59:900–5 https://www.ncbi.nlm.nih.gov/pubmed/16033610 | Daily Eating Occasions Not Reported
899 | Torbahn G, Gellhaus I, Koch B, von Kries R, Obermeier V, Holl RW, Fink K, van Egmond-Frohlich A. Reduction of Portion Size and Eating Rate Is Associated with BMI-SDS Reduction in Overweight and Obese Children and Adolescents: Results on Eating and Nutrition Behaviour from the Observational KgAS Study. Obes Facts. 2017. 10:503–516 https://www.ncbi.nlm.nih.gov/pubmed/29084405 | Intervention/Exposure
900 | Torjesen I. The Finland experience: leading the way in prevention. Circulation. 2007. 115:f11–2 https://www.ncbi.nlm.nih.gov/pubmed/17245844 | Study Design
901 | Toschke AM, Kuchenhoff H, Koletzko B, von Kries R. Meal frequency and childhood obesity. Obes Res. 2005. 13:1932–8 https://www.ncbi.nlm.nih.gov/pubmed/16339125 | Study Design
902 | Toschke AM, Thorsteinsdottir KH, von Kries R. Meal frequency, breakfast consumption and childhood obesity. Int J Pediatr Obes. 2009. 4:242–8 https://www.ncbi.nlm.nih.gov/pubmed/19922038 | Study Design
903 | Toyoshima H, Masuoka N, Hashimoto S, Otsuka R, Sasaki S, Tamakoshi K, Yatsuya H. Effect of the interaction between mental stress and eating pattern on body mass index gain in healthy Japanese male workers. J Epidemiol. 2009. 19:88–93 https://www.ncbi.nlm.nih.gov/pubmed/19265270 | Intervention/Exposure
904 | Trabelsi K, el Abed K, Stannard SR, Jammoussi K, Zeghal KM, Hakim A. Effects of fed- versus fasted-state aerobic training during Ramadan on body composition and some metabolic parameters in physically active men. Int J Sport Nutr Exerc Metab. 2012. 22:11–8 https://www.ncbi.nlm.nih.gov/pubmed/22248495 | Daily Eating Occasions Not Reported
905 | Trabelsi K, el Abed K, Trepanowski JF, Stannard SR, Ghlissi Z, Ghozzi H, et al. Effects of Ramadan Fasting on Biochemical and Anthropometric Parameters in Physically Active Men. Asian Journal of Sports Medicine. 2011;2(3):134–44. https://www.ncbi.nlm.nih.gov/pubmed/22375232. | Daily Eating Occasions Not Reported
906 | Trabelsi K, Stannard SR, Maughan RJ, Jammoussi K, Zeghal K, Hakim A. Effect of resistance training during Ramadan on body composition and markers of renal function, metabolism, inflammation, and immunity in recreational bodybuilders. Int J Sport Nutr Exerc Metab. 2012. 22:267–75 https://www.ncbi.nlm.nih.gov/pubmed/22855788 | Daily Eating Occasions Not Reported
907 | Traub M, Lauer R, Kesztyus T, Wartha O, Steinacker JM, Kesztyus D. Skipping breakfast, overconsumption of soft drinks and screen media: longitudinal analysis of the combined influence on weight development in primary schoolchildren. BMC Public Health. 2018. 18:363 https://www.ncbi.nlm.nih.gov/pubmed/29548323 | Daily Eating Occasions Not Reported
908 | Tremblay A, Lepage C, Panahi S, Couture C, Drapeau V. Adaptations to a diet-based weight-reducing programme in obese women resistant to weight loss. Clin Obes. 2015. 5:145–53 https://www.ncbi.nlm.nih.gov/pubmed/25872975 | Intervention/Exposure, Daily Eating Occasions Not Reported
909 | Trepanowski J, Kroeger C, Barnosky A, Hoddy K, Varady K. Alternateday fasting and daily calorie restriction similarly affect visceral adiposity and circulating inflammatory cytokine concentrations. FASEB journal. 2015;29(Suppl. 1). | Study Design, Publication Status
910 | Trepanowski J, Kroeger C, Klempel M, Calvo Y, Varady K. Alternateday fasting versus daily calorie restriction for weight loss and cardio-protection. FASEB journal. 2014;28(Suppl. 1). | Study Design, Publication Status
911 | Trepanowski JF, Kroeger CM, Barnosky A, Klempel M, Bhutani S, Hoddy KK, Rood J, Ravussin E, Varady KA. Effects of alternate-day fasting or daily calorie restriction on body composition, fat distribution, and circulating adipokines: Secondary analysis of a randomized controlled trial. Clin Nutr. 2018. 37:1871–1878 https://www.ncbi.nlm.nih.gov/pubmed/29258678 | Daily Eating Occasions Not Reported, Size of Study Groups
912 | Trepanowski JF, Kroeger CM, Barnosky A, Klempel MC, Bhutani S, Hoddy KK, Gabel K, Freels S, Rigdon J, Rood J, Ravussin E, Varady KA. Effect of Alternate-Day Fasting on Weight Loss, Weight Maintenance, and Cardioprotection Among Metabolically Healthy Obese Adults: A Randomized Clinical Trial. JAMA Intern Med. 2017. 177:930–938 https://www.ncbi.nlm.nih.gov/pubmed/28459931 | Intervention/Exposure, Daily Eating Occasions Not Reported, Comparator
913 | Trepanowski JF, Kabir MM, Alleman Jr RJ, Bloomer RJ. A 21-day Daniel fast with or without krill oil supplementation improves anthropometric parameters and the cardiometabolic profile in men and women. Nutrition & metabolism. 2012;9(1):82–8. https://www.ncbi.nlm.nih.gov/pubmed/22971786. | Intervention/Exposure, Comparator
914 | Trotti R, Rondanelli M, Cuzzoni G, Ferrari E, dEril GM. Circadian temporal organization of lipidic fractions in elderly people. Entrainment to the dietary schedule. Aging Clin Exp Res. 2002. 14:94–9 https://www.ncbi.nlm.nih.gov/pubmed/12092790 | Study Design
915 | Tucker JM, DeFrang R, Orth J, Wakefield S, Howard K. Evaluation of a Primary Care Weight Management Program in Children Aged 2(-)5 years: Changes in Feeding Practices, Health Behaviors, and Body Mass Index. Nutrients. 2019;11(3). https://www.ncbi.nlm.nih.gov/pubmed/30818772. | Intervention/Exposure
916 | Turconi G, Guarcello M, Maccarini L, Cignoli F, Setti S, Bazzano R, Roggi C. Eating habits and behaviors, physical activity, nutritional and food safety knowledge and beliefs in an adolescent Italian population. J Am Coll Nutr. 2008. 27:31–43 https://www.ncbi.nlm.nih.gov/pubmed/18460479 | Study Design
917 | Turner-McGrievy GM, Dunn CG, Wilcox S, Boutte AK, Hutto B, Hoover A, Muth E. Defining Adherence to Mobile Dietary Self-Monitoring and Assessing Tracking Over Time: Tracking at Least Two Eating Occasions per Day Is Best Marker of Adherence within Two Different Mobile Health Randomized Weight Loss Interventions. J Acad Nutr Diet. 2019. 119:1516–1524 https://www.ncbi.nlm.nih.gov/pubmed/31155473 | Intervention/Exposure
918 | Uemura M, Yatsuya H, Hilawe EH, Li Y, Wang C, Chiang C, Otsuka R, Toyoshima H, Tamakoshi K, Aoyama A. Breakfast Skipping is Positively Associated With Incidence of Type 2 Diabetes Mellitus: Evidence From the Aichi Workers Cohort Study. J Epidemiol. 2015. 25:351–8 https://www.ncbi.nlm.nih.gov/pubmed/25787236 | Daily Eating Occasions Not Reported
919 | Unalacak M, Kara IH, Baltaci D, Erdem O, Bucaktepe PG. Effects of Ramadan fasting on biochemical and hematological parameters and cytokines in healthy and obese individuals. Metab Syndr Relat Disord. 2011. 9:15761 https://www.ncbi.nlm.nih.gov/pubmed/21235381 | Daily Eating Occasions Not Reported
920 | Utter J, Denny S, Robinson E, Fleming T, Ameratunga S, Grant S. Family meals among New Zealand young people: relationships with eating behaviors and body mass index. J Nutr Educ Behav. 2013. 45:3–11 https://www.ncbi.nlm.nih.gov/pubmed/23110750 | Study Design
921 | Uusitalo U, Arkkola T, Ovaskainen ML, Kronberg-Kippila C, Kenward MG, Veijola R, Simell O, Knip M, Virtanen SM. Unhealthy dietary patterns are associated with weight gain during pregnancy among Finnish women. Public Health Nutr. 2009. 12:2392–9 https://www.ncbi.nlm.nih.gov/pubmed/19323867 | Intervention/Exposure
922 | Vaitkeviciute J, Petrauskiene A. The Associations between Body Mass Index of Seven- and Eight-Year-Old Children, Dietary Behaviour and Nutrition-Related Parenting Practices. Medicina. 2019;55(1). https://www.ncbi.nlm.nih.gov/pubmed/30669687. | Study Design
923 | van den Berg P, Neumark-Sztainer D, Hannan PJ, Haines J. Is dieting advice from magazines helpful or harmful? Five-year associations with weight-control behaviors and psychological outcomes in adolescents. Pediatrics. 2007. 119:e30–7 https://www.ncbi.nlm.nih.gov/pubmed/17200254 | Intervention/Exposure
924 | van der Crabben SN, Allick G, Ackermans MT, Endert E, Romijn JA, Sauerwein HP. Prolonged fasting induces peripheral insulin resistance, which is not ameliorated by high-dose salicylate. J Clin Endocrinol Metab. 2008. 93:638–41 https://www.ncbi.nlm.nih.gov/pubmed/18056775 | Intervention/Exposure
925 | van der Wijden CL, Steinbach S, van der Ploeg HP, van Mechelen W, van Poppel MN. A longitudinal study on the relationship between eating style and gestational weight gain. Appetite. 2014. 83:304–8 https://www.ncbi.nlm.nih.gov/pubmed/25218880 | Intervention/Exposure
926 | van Ewijk RJ, Painter RC, Roseboom TJ. Associations of prenatal exposure to Ramadan with small stature and thinness in adulthood: results from a large Indonesian population-based study. Am J Epidemiol. 2013;177(8):729–36. https://www.ncbi.nlm.nih.gov/pubmed/23486307. | Daily Eating Occasions Not Reported, Outcome
927 | van Ewijk RJ, Painter RC, Roseboom TJ. Associations of prenatal exposure to Ramadan with small stature and thinness in adulthood: results from a large Indonesian population-based study. Am J Epidemiol. 2013. 177:729–36 https://www.ncbi.nlm.nih.gov/pubmed/23486307 | Intervention/Exposure, Daily Eating Occasions Not Reported
928 | van Herpen NA, Sell H, Eckel J, Schrauwen P, Mensink RP. Prolonged fasting and the effects on biomarkers of inflammation and on adipokines in healthy lean men. Horm Metab Res. 2013. 45:378–82 https://www.ncbi.nlm.nih.gov/pubmed/23235922 | Daily Eating Occasions Not Reported
929 | Van Tine ML, McNicholas F, Safer DL, Agras WS. Follow-up of selective eaters from childhood to adulthood. Eat Behav. 2017. 26:61–65 https://www.ncbi.nlm.nih.gov/pubmed/28152419 | Intervention/Exposure
930 | van Veen MR, van Hasselt PM, de Sain-van der Velden MG, Verhoeven N, Hofstede FC, de Koning TJ, Visser G. Metabolic profiles in children during fasting. Pediatrics. 2011. 127:e1021–7 https://www.ncbi.nlm.nih.gov/pubmed/21422093 | Daily Eating Occasions Not Reported
931 | Vander Wal JS, Waller SM, Klurfeld DM, McBurney MI, Cho S, Kapila M, Dhurandhar NV. Effect of a post-dinner snack and partial meal replacement program on weight loss. Int J Food Sci Nutr. 2006. 57:97–106 https://www.ncbi.nlm.nih.gov/pubmed/16849118 | Daily Eating Occasions Not Reported
932 | Vandeweghe L, Verbeken S, Vervoort L, Moens E, Braet C. Reward sensitivity and body weight: the intervening role of food responsive behavior and external eating. Appetite. 2017. 112:150–156 https://www.ncbi.nlm.nih.gov/pubmed/28108344 | Study Design
933 | Vanelli M, Iovane B, Bernardini A, Chiari G, Errico MK, Gelmetti C, Corchia M, Ruggerini A, Volta E, Rossetti S. Breakfast habits of 1,202 northern Italian children admitted to a summer sport school. Breakfast skipping is associated with overweight and obesity. Acta Biomed. 2005. 76:79–85 https://www.ncbi.nlm.nih.gov/pubmed/16350552 | Study Design, Daily Eating Occasions Not Reported
934 | Vanelli M, Monti G, Volta E, Finestrella V, Gkliati D, Cangelosi M, Caragnulo R, Vitale M, Ingrosso L, Scazzina F. “GIOCAMPUS” - An effective school-based intervention for breakfast promotion and overweight risk reduction. Acta Biomed. 2014. 84:181–8 https://www.ncbi.nlm.nih.gov/pubmed/24458162 | Daily Eating Occasions Not Reported
935 | Varady K. Alternate-day fasting. Menopause. 2016. 23:1368 | Publication Status
936 | Varady KA, Bhutani S, Church EC, Klempel MC. Short-term modified alternate-day fasting: a novel dietary strategy for weight loss and cardioprotection in obese adults. Am J Clin Nutr. 2009. 90:1138–43 https://www.ncbi.nlm.nih.gov/pubmed/19793855 | Study Design, Daily Eating Occasions Not Reported
937 | Varady KA, Bhutani S, Klempel MC, Kroeger CM, Trepanowski JF, Haus JM, Hoddy KK, Calvo Y. Alternate day fasting for weight loss in normal weight and overweight subjects: a randomized controlled trial. Nutr J. 2013. 12:146 https://www.ncbi.nlm.nih.gov/pubmed/24215592 | Daily Eating Occasions Not Reported, Comparator
938 | Varady KA, Bhutani S, Klempel MC, Lamarche B. Improvements in LDL particle size and distribution by short-term alternate day modified fasting in obese adults. Br J Nutr. 2011. 105:580–3 https://www.ncbi.nlm.nih.gov/pubmed/20880415 | Intervention/Exposure, Daily Eating Occasions Not Reported
939 | Varady KA, Dam VT, Klempel MC, Horne M, Cruz R, Kroeger CM, Santosa S. Corrigendum: Effects of weight loss via high fat vs. low fat alternate day fasting diets on free fatty acid profiles. Sci Rep. 2015. 5:8806 https://www.ncbi.nlm.nih.gov/pubmed/26244425 | Study Design, Publication Status
940 | Varady KA, Dam VT, Klempel MC, Horne M, Cruz R, Kroeger CM, Santosa S. Effects of weight loss via high fat vs. low fat alternate day fasting diets on free fatty acid profiles. Sci Rep. 2015. 5:7561 https://www.ncbi.nlm.nih.gov/pubmed/25557754 | Intervention/Exposure, Daily Eating Occasions Not Reported
941 | Varady KA, Gabel K. Dietary adherence and macronutrient intake during 12 months of alternate day fasting. FASEB journal. 2017;31(1). | Study Design, Publication Status
942 | Varady KA, Hoddy KK, Kroeger CM, Trepanowski JF, Klempel MC, Barnosky A, Bhutani S. Determinants of weight loss success with alternate day fasting. Obes Res Clin Pract. 2016. 10:476–80 https://www.ncbi.nlm.nih.gov/pubmed/26385599 | Intervention/Exposure
943 | Vardarli MC, Hammes HP, Vardarli I. Possible metabolic impact of Ramadan fasting in healthy men. Turk J Med Sci. 2014. 44:1010–20 https://www.ncbi.nlm.nih.gov/pubmed/25552155 | Intervention/Exposure, Daily Eating Occasions Not Reported
944 | Vatanparast H, Islam N, Patil RP, Shafiee M, Smith J, Whiting S. Snack Consumption Patterns among Canadians. Nutrients. 2019;11(5). https://www.ncbi.nlm.nih.gov/pubmed/31126080. | Study Design
945 | Veloso SusanaM, Matos MargaridaG, Marina Carvalho, Diniz JosA. Psychosocial Factors of Different Health Behaviour Patterns in Adolescents: Association with Overweight and Weight Control Behaviours. Journal of Obesity. 2012. 2012:1–10 http://search.ebscohost.com/login.aspx?direct=true&db=jlh&AN=104278012&site=ehost-live | Study Design
946 | Veltsista A, Laitinen J, Sovio U, Roma E, Jarvelin MR, Bakoula C. Relationship between eating behavior, breakfast consumption, and obesity among Finnish and Greek adolescents. J Nutr Educ Behav. 2010. 42:417–21 https://www.ncbi.nlm.nih.gov/pubmed/20729150 | Study Design
947 | Vendelbo MH, Moller AB, Christensen B, Nellemann B, Clasen BF, Nair KS, Jorgensen JO, Jessen N, Moller N. Fasting increases human skeletal muscle net phenylalanine release and this is associated with decreased mTOR signaling. PLoS One. 2014. 9:e102031 https://www.ncbi.nlm.nih.gov/pubmed/25020061 | Intervention/Exposure, Daily Eating Occasions Not Reported
948 | Vergetaki A, Linardakis M, Papadaki A, Kafatos A. Presence of metabolic syndrome and cardiovascular risk factors in adolescents and University students in Crete (Greece), according to different levels of snack consumption. Appetite. 2011. 57:278–85 https://www.ncbi.nlm.nih.gov/pubmed/21640150 | Study Design
949 | Verhoef SP, Camps SG, Gonnissen HK, Westerterp KR, Westerterp-Plantenga MS. Concomitant changes in sleep duration and body weight and body composition during weight loss and 3-mo weight maintenance. Am J Clin Nutr. 2013. 98:25–31 https://www.ncbi.nlm.nih.gov/pubmed/23697706 | Intervention/Exposure, Daily Eating Occasions Not Reported
950 | Versteeg RI, Ackermans MT, Nederveen AJ, Fliers E, Serlie MJ, la Fleur SE. Meal timing effects on insulin sensitivity and intrahepatic triglycerides during weight loss. Int J Obes. 2018. 42:156–162 https://www.ncbi.nlm.nih.gov/pubmed/28811653 | Comparator
951 | Versteeg RI, Schrantee A, Adriaanse SM, Unmehopa UA, Booij J, Reneman L, Fliers E, la Fleur SE, Serlie MJ. Timing of caloric intake during weight loss differentially affects striatal dopamine transporter and thalamic serotonin transporter binding. Faseb j. 2017. 31:4545–4554 https://www.ncbi.nlm.nih.gov/pubmed/28679529 | Intervention/Exposure, Daily Eating Occasions Not Reported, Comparator
952 | Veugelers PJ, Fitzgerald AL. Prevalence of and risk factors for childhood overweight and obesity. CMAJ: Canadian Medical Association Journal. 2005;173(6):607–13. https://www.ncbi.nlm.nih.gov/pubmed/16157724. | Study Design
953 | Vieira Musse GN, Moreira T, Ayumi Kimura M, Pereira FWL, Okoshi K, Garcia Zanati S, et al. Skipping breakfast concomitant with late-night dinner eating is associated with worse outcomes following ST-segment elevation myocardial infarction. Eur J Prev Cardiol. 2019:2047487319839546. https://www.ncbi.nlm.nih.gov/pubmed/30995859. | Study Design, Publication Status, Health Status
954 | Vieten C, Laraia BA, Kristeller J, Adler N, Coleman-Phox K, Bush NR, Wahbeh H, Duncan LG, Epel E. The mindful moms training: development of a mindfulness-based intervention to reduce stress and overeating during pregnancy. BMC Pregnancy Childbirth. 2018. 18:201 https://www.ncbi.nlm.nih.gov/pubmed/29859038 | Intervention/Exposure
955 | Vigna L, Brunani A, Brugnera A, Grossi E, Compare A, Tirelli AS, Conti DM, Agnelli GM, Andersen LL, Buscema M, Riboldi L. Determinants of metabolic syndrome in obese workers: gender differences in perceived job-related stress and in psychological characteristics identified using artificial neural networks. Eat Weight Disord. 2019. 24:73–81 https://www.ncbi.nlm.nih.gov/pubmed/29987776 | Intervention/Exposure
956 | Vik FN, Overby NC, Lien N, Bere E. Number of meals eaten in relation to weight status among Norwegian adolescents. Scand J Public Health. 2010. 38:13–8 https://www.ncbi.nlm.nih.gov/pubmed/21062835 | Study Design
957 | Vilela S, Oliveira A, Severo M, Lopes C. Chrono-Nutrition: The Relationship between Time-of-Day Energy and Macronutrient Intake and Childrens Body Weight Status. J Biol Rhythms. 2019. 34:332–342 https://www.ncbi.nlm.nih.gov/pubmed/30917726 | Daily Eating Occasions Not Reported
958 | Vinales KL, Schlogl M, Reinhardt M, Thearle MS, Krakoff J, Piaggi P. Cycling Efficiency During Incremental Cycle Ergometry After 24 Hours of Overfeeding or Fasting. Obesity. 2018. 26:368–377 https://www.ncbi.nlm.nih.gov/pubmed/29276860 | Intervention/Exposure, Size of Study Groups
959 | Vinter CA, Jørgensen JS, Ovesen P, Beck-Nielsen H, Skytthe A, Jensen DM. Metabolic effects of lifestyle intervention in obese pregnant women. Results from the randomized controlled trial ‘Lifestyle in Pregnancy’ (LiP). Diabetic medicine. 2014;31(11):1323–30. https://www.ncbi.nlm.nih.gov/pubmed/24989831. | Intervention/Exposure
960 | Viskaal-van Dongen M, Kok FJ, de Graaf C. Effects of snack consumption for 8 weeks on energy intake and body weight. Int J Obes. 2010. 34:319–26 https://www.ncbi.nlm.nih.gov/pubmed/19935746 | Eating Frequency Data Collection
961 | von Katzler R, Zyriax BC, Jagemann B, Westenhoefer J, Jensen HJ, Harth V, Oldenburg M. Lifestyle behaviour and prevalence of cardiovascular risk factors - a pilot study comparing Kiribati and European seafarers. BMC Public Health. 2019. 19:855 https://www.ncbi.nlm.nih.gov/pubmed/31262273 | Intervention/Exposure
962 | Wagner R, Oberste-Berghaus C, Herpertz S, Blum WF, Pelz B, Hebebrand J, Senf W, Mann K, Albers N. Time relationship between circadian variation of serum levels of leptin, insulin and cortisol in healthy subjects. Horm Res. 2000. 54:174–80 https://www.ncbi.nlm.nih.gov/pubmed/11416234 | Intervention/Exposure, Daily Eating Occasions Not Reported
963 | Wainstein J, Boaz M, Bar-Dayan Y, Jakubowicz D. Influence of meal timing on glucose metabolism and hyperandrogenism in lean women with polycystic ovary syndrome. Diabetologia. 2012. 55:S235–S236 | Health Status
964 | Waller CE, Du S, Popkin BM. Patterns of overweight, inactivity, and snacking in Chinese children. Obes Res. 2003. 11:957–61 https://www.ncbi.nlm.nih.gov/pubmed/12917500 | Study Design
965 | Waller SM, Vander Wal JS, Klurfeld DM, McBurney MI, Cho S, Bijlani S, Dhurandhar NV. Evening ready-to-eat cereal consumption contributes to weight management. J Am Coll Nutr. 2004. 23:316–21 https://www.ncbi.nlm.nih.gov/pubmed/15310735 | Intervention/Exposure, Daily Eating Occasions Not Reported
966 | Wang P, Lu MC, Yu CW, Yan YH. Influence of the time of day and fasting duration on glucose level following a 1hour, 50-gram glucose challenge test in pregnant women. PLoS One. 2014. 9:e112526 https://www.ncbi.nlm.nih.gov/pubmed/25393415 | Intervention/Exposure, Daily Eating Occasions Not Reported
967 | Wang S, Schwartz MB, Shebl FM, Read M, Henderson KE, Ickovics JR. School breakfast and body mass index: a longitudinal observational study of middle school students. Pediatr Obes. 2017. 12:213–220 https://www.ncbi.nlm.nih.gov/pubmed/26989876 | Daily Eating Occasions Not Reported
968 | Washburn RL, Cox JE, Muhlestein JB, May HT, Carlquist JF, Le VT, et al. Pilot Study of Novel Intermittent Fasting Effects on Metabolomic and Trimethylamine N-oxide Changes During 24-hour Water-Only Fasting in the FEELGOOD Trial. Nutrients. 2019;11(2). https://www.ncbi.nlm.nih.gov/pubmed/30678028. | Daily Eating Occasions Not Reported, Outcome
969 | Watanabe Y, Saito I, Henmi I, Yoshimura K, Maruyama K, Yamauchi K, Matsuo T, Kato T, Tanigawa T, Kishida T, Asada Y. Skipping Breakfast is Correlated with Obesity. J Rural Med. 2014. 9:51–8 https://www.ncbi.nlm.nih.gov/pubmed/25648986 | Study Design
970 | Webb JB, Hardin AS. A preliminary evaluation of BMI status in moderating changes in body composition and eating behavior in ethnically-diverse first-year college women. Eat Behav. 2012. 13:402–5 https://www.ncbi.nlm.nih.gov/pubmed/23121798 | Intervention/Exposure
971 | Wegman MP, Guo MH, Bennion DM, Shankar MN, Chrzanowski SM, Goldberg LA, Xu J, Williams TA, Lu X, Hsu SI, Anton SD, Leeuwenburgh C, Brantly ML. Practicality of intermittent fasting in humans and its effect on oxidative stress and genes related to aging and metabolism. Rejuvenation Res. 2015. 18:162–72 https://www.ncbi.nlm.nih.gov/pubmed/25546413 | Intervention/Exposure, Daily Eating Occasions Not Reported
972 | Wehrens SMT, Christou S, Isherwood C, Middleton B, Gibbs MA, Archer SN, Skene DJ, Johnston JD. Meal Timing Regulates the Human Circadian System. Curr Biol. 2017. 27:1768–1775.e3 https://www.ncbi.nlm.nih.gov/pubmed/28578930 | Intervention/Exposure, Daily Eating Occasions Not Reported, Comparator
973 | Wei M, Brandhorst S, Shelehchi M, Mirzaei H, Cheng CW, Budniak J, et al. Fasting-mimicking diet and markers/risk factors for aging, diabetes, cancer, and cardiovascular disease. Sci Transl Med. 2017;9(377). https://www.ncbi.nlm.nih.gov/pubmed/28202779. | Daily Eating Occasions Not Reported
974 | Wengreen HJ, Moncur C. Change in diet, physical activity, and body weight among young-adults during the transition from high school to college. Nutr J. 2009. 8:32 https://www.ncbi.nlm.nih.gov/pubmed/19624820 | Intervention/Exposure, Daily Eating Occasions Not Reported
975 | Wennberg M, Gustafsson PE, Wennberg P, Hammarstrom A. Irregular eating of meals in adolescence and the metabolic syndrome in adulthood: results from a 27-year prospective cohort. Public Health Nutr. 2016. 19:667–73 https://www.ncbi.nlm.nih.gov/pubmed/25936413 | Intervention/Exposure, Daily Eating Occasions Not Reported
976 | Wennberg M, Gustafsson PE, Wennberg P, Hammarstrom A. Poor breakfast habits in adolescence predict the metabolic syndrome in adulthood. Public Health Nutr. 2015. 18:122–9 https://www.ncbi.nlm.nih.gov/pubmed/24468205 | Daily Eating Occasions Not Reported
977 | Werneck AO, Agostinete RR, Cayres SU, Urban JB, Wigna A, Chagas LGM, et al. Association between Cluster of Lifestyle Behaviors and HOMA-IR among Adolescents: ABCD Growth Study. Medicina. 2018;54(6). https://www.ncbi.nlm.nih.gov/pubmed/30513771. | Study Design
978 | Westenhoefer J, von Falck B, Stellfeldt A, Fintelmann S. Behavioural correlates of successful weight reduction over 3 y. Results from the Lean Habits Study. Int J Obes Relat Metab Disord. 2004. 28:334–5 https://www.ncbi.nlm.nih.gov/pubmed/14647175 | Intervention/Exposure, Daily Eating Occasions Not Reported
979 | Westerterp-Plantenga MS, Goris AH, Meijer EP, Westerterp KR. Habitual meal frequency in relation to resting and activity-induced energy expenditure in human subjects: the role of fat-free mass. Br J Nutr. 2003. 90:643–9 https://www.ncbi.nlm.nih.gov/pubmed/13129471 | Study Design
980 | Westerterp-Plantenga MS, Kovacs EM, Melanson KJ. Habitual meal frequency and energy intake regulation in partially temporally isolated men. Int J Obes Relat Metab Disord. 2002. 26:102–10 https://www.ncbi.nlm.nih.gov/pubmed/11791154 | Outcome
981 | White MA, Martin PD, Newton RL, Walden HM, York-Crowe EE, Gordon ST, Ryan DH, Williamson DA. Mediators of weight loss in a family-based intervention presented over the internet. Obes Res. 2004. 12:1050–9 https://www.ncbi.nlm.nih.gov/pubmed/15292468 | Intervention/Exposure, Daily Eating Occasions Not Reported
982 | Whitelock V, Kersbergen I, Higgs S, Aveyard P, Halford JCG, Robinson E. A smartphone based attentive eating intervention for energy intake and weight loss: results from a randomised controlled trial. BMC Public Health. 2019. 19:611 https://www.ncbi.nlm.nih.gov/pubmed/31113400 | Intervention/Exposure
983 | Widhalm K, Pppelmeyer C, Helk O. The Effect of Alternate-Day Fasting (ADF) on Weight Loss, Metabolic Parameters and Psychological Characteristics. Aktuelle ernahrungsmedizin. 2017;42(3):188–92. | Intervention/Exposure, Daily Eating Occasions Not Reported
984 | Widome R, Neumark-Sztainer D, Hannan PJ, Haines J, Story M. Eating when there is not enough to eat: eating behaviors and perceptions of food among food-insecure youths. Am J Public Health. 2009. 99:822–8 https://www.ncbi.nlm.nih.gov/pubmed/19299675 | Study Design
985 | Wijngaarden MA, van der Zon GC, van Dijk KW, Pijl H, Guigas B. Effects of prolonged fasting on AMPK signaling, gene expression, and mitochondrial respiratory chain content in skeletal muscle from lean and obese individuals. Am J Physiol Endocrinol Metab. 2013. 304:E1012–21 https://www.ncbi.nlm.nih.gov/pubmed/23512807 | Intervention/Exposure, Daily Eating Occasions Not Reported
986 | Wijtzes AI, Jansen W, Bouthoorn SH, van Lenthe FJ, Franco OH, Hofman A, Jaddoe VW, Raat H. Meal-Skipping Behaviors and Body Fat in 6-Year-Old Children. J Pediatr. 2016. 168:118–25.e2 https://www.ncbi.nlm.nih.gov/pubmed/26520914 | Daily Eating Occasions Not Reported
987 | Witbracht M, Keim NL, Forester S, Widaman A, Laugero K. Female breakfast skippers display a disrupted cortisol rhythm and elevated blood pressure. Physiol Behav. 2015. 140:215–21 https://www.ncbi.nlm.nih.gov/pubmed/25545767 | Study Design, Daily Eating Occasions Not Reported
988 | Wong T, Hirahatake K, Nguyen T, Carlos AC, Odegaard AO. The effect of a time restricted eating approach vs. standard heart healthy dietary counseling on cardiometabolic health measures in adults with abdominal obesity: a randomized pilot trial. Circulation. 2019;139. | Study Design, Publication Status
989 | Woodruff SJ, Hanning RM, Lambraki I, Storey KE, McCargar L. Healthy Eating Index-C is compromised among adolescents with body weight concerns, weight loss dieting, and meal skipping. Body Image. 2008. 5:404–8 https://www.ncbi.nlm.nih.gov/pubmed/18640883 | Study Design
990 | Wu CH, Lin CY, Hsieh YP, Strong C, Meshki C, Lin YC, Tsai MC. Dietary behaviors mediate the association between food insecurity and obesity among socioeconomically disadvantaged youth. Appetite. 2019. 132:275–281 https://www.ncbi.nlm.nih.gov/pubmed/30327150 | Study Design, Daily Eating Occasions Not Reported
991 | Wuenstel JW, Kowalkowska J, Wadolowska L, Slowinska MA, Niedzwiedzka E, Kurp L. Habitual eating of breakfast, consumption frequency of selected food and overweight prevalence in adolescents from various age groups. Dev Period Med. 2015. 19:193–201 https://www.ncbi.nlm.nih.gov/pubmed/26384123 | Study Design, Daily Eating Occasions Not Reported
992 | Wylie J, Barr S, Jeanes Y. Eating frequency and snacking habits in women with polycystic ovary syndrome. Journal of Human Nutrition & Dietetics. 2009. 22:274–275 | Health Status
993 | Wynn P, Wynn J. Smairt Snacking BYPASS JUNK FOOD AND PICK HEALTHY GO-TO SNACKS. Diabetes Self Manag. 2017. 34:70–71 https://www.ncbi.nlm.nih.gov/pubmed/29714853 | Study Design, Intervention/Exposure
994 | Xiao Q, Garaulet M, Fajl Scheer. Meal timing and obesity: interactions with macronutrient intake and chronotype. Int J Obes (Lond). 2019. 43:1701–1711 https://www.ncbi.nlm.nih.gov/pubmed/30705391 | Daily Eating Occasions Not Reported, Eating Frequency Data Collection
995 | Yamane M, Ekuni D, Mizutani S, Kataoka K, Sakumoto-Kataoka M, Kawabata Y, Omori C, Azuma T, Tomofuji T, Iwasaki Y, Morita M. Relationships between eating quickly and weight gain in Japanese university students: a longitudinal study. Obesity (Silver Spring). 2014. 22:2262–6 https://www.ncbi.nlm.nih.gov/pubmed/25044853 | Daily Eating Occasions Not Reported
996 | Yannakoulia M, Ntalla I, Papoutsakis C, Farmaki AE, Dedoussis GV. Consumption of vegetables, cooked meals, and eating dinner is negatively associated with overweight status in children. J Pediatr. 2010. 157:815–20 https://www.ncbi.nlm.nih.gov/pubmed/20955852 | Study Design
997 | Yannakoulia M, Sitara M, Matalas AL. Reported eating behavior and attitudes improvement after a nutrition intervention program in a group of young female dancers. Int J Sport Nutr Exerc Metab. 2002. 12:24–32 https://www.ncbi.nlm.nih.gov/pubmed/11993620 | Intervention/Exposure, Daily Eating Occasions Not Reported
998 | Yildiran H, Mercanligil SM. Does increasing meal frequency improve weight loss and some biochemical parameters in overweight/obese females?. Nutr Hosp. 2019. 36:66–72 https://www.ncbi.nlm.nih.gov/pubmed/30836763 | Eating Frequency Data Collection
999 | Yoncheva YN, Castellanos FX, Pizinger T, Kovtun K, St-Onge MP. Sleep and meal-time misalignment alters functional connectivity: a pilot resting-state study. Int J Obes (Lond). 2016. 40:1813–1816 https://www.ncbi.nlm.nih.gov/pubmed/27478925 | Daily Eating Occasions Not Reported, Comparator, Size of Study Groups
1000 | Yoo KB, Suh HJ, Lee M, Kim JH, Kwon JA, Park EC. Breakfast eating patterns and the metabolic syndrome: the Korea National Health and Nutrition Examination Survey (KNHANES) 2007-2009. Asia Pac J Clin Nutr. 2014. 23:128–37 https://www.ncbi.nlm.nih.gov/pubmed/24561981 | Study Design
1001 | Yoshida J, Eguchi E, Nagaoka K, Ito T, Ogino K. Association of night eating habits with metabolic syndrome and its components: a longitudinal study. BMC Public Health. 2018. 18:1366 https://www.ncbi.nlm.nih.gov/pubmed/30537972 | Daily Eating Occasions Not Reported
1002 | Yoshimura E, Hatamoto Y, Yonekura S, Tanaka H. Skipping breakfast reduces energy intake and physical activity in healthy women who are habitual breakfast eaters: A randomized crossover trial. Physiol Behav. 2017. 174:89–94 https://www.ncbi.nlm.nih.gov/pubmed/28284879 | Daily Eating Occasions Not Reported, Outcome
1003 | Yucel A, Degirmenci B, Acar M, Albayrak R, Haktanir A. The effect of fasting month of Ramadan on the abdominal fat distribution: assessment by computed tomography. Tohoku J Exp Med. 2004. 204:179–87 https://www.ncbi.nlm.nih.gov/pubmed/15502416 | Intervention/Exposure, Daily Eating Occasions Not Reported
1004 | Zakrzewski-Fruer JK, Plekhanova T, Mandila D, Lekatis Y, Tolfrey K. Effect of breakfast omission and consumption on energy intake and physical activity in adolescent girls: a randomised controlled trial. Br J Nutr. 2017. 118:392–400 https://www.ncbi.nlm.nih.gov/pubmed/28901889 | Daily Eating Occasions Not Reported
1005 | Zakrzewski-Fruer JK, Wells EK, Crawford NSG, Afeef SMO, Tolfrey K. Physical Activity Duration but Not Energy Expenditure Differs between Daily and Intermittent Breakfast Consumption in Adolescent Girls: A Randomized Crossover Trial. J Nutr. 2018. 148:236–244 https://www.ncbi.nlm.nih.gov/pubmed/29490105 | Outcome
1006 | Zalewska M, Maciorkowska E. Dietary Habits and Physical Activity of 18-Year-Old Adolescents in Relation to Overweight and Obesity. Iran J Public Health. 2019. 48:864–872 https://www.ncbi.nlm.nih.gov/pubmed/31523643 | Study Design
1007 | Zare A, Hajhashemi M, Hassan ZM, Zarrin S, Pourpak Z, Moin M, Salarilak S, Masudi S, Shahabi S. Effect of Ramadan fasting on serum heat shock protein 70 and serum lipid profile. Singapore Med J. 2011. 52:491–5 https://www.ncbi.nlm.nih.gov/pubmed/21808959 | Daily Eating Occasions Not Reported
1008 | Zarrouk N, Hammouda O, Latiri I, Adala H, Bouhlel E, Rebai H, Dogui M. Ramadan fasting does not adversely affect neuromuscular performances and reaction times in trained karate athletes. J Int Soc Sports Nutr. 2016. 13:18 https://www.ncbi.nlm.nih.gov/pubmed/27099568 | Daily Eating Occasions Not Reported, Size of Study Groups
1009 | Zarrouk N, Hug F, Hammouda O, Rebai H, Tabka Z, Dogui M, Bouhlel E. Effect of Ramadan intermittent fasting on body composition and neuromuscular performance in young athletes: A pilot study. Biological Rhythm Research. 2013. 44:697–709 | Daily Eating Occasions Not Reported
1010 | Zaveri S, Drummond S. The effect of including a conventional snack (cereal bar) and a nonconventional snack (almonds) on hunger, eating frequency, dietary intake and body weight. J Hum Nutr Diet. 2009. 22:461–8 https://www.ncbi.nlm.nih.gov/pubmed/19743983 | Comparator, Size of Study Groups
1011 | Zerguini Y, Dvorak J, Maughan RJ, Leiper JB, Bartagi Z, Kirkendall DT, Al-Riyami M, Junge A. Influence of Ramadan fasting on physiological and performance variables in football players: summary of the F-MARC 2006 Ramadan fasting study. J Sports Sci. 2008. 26 Suppl 3:S3–6 https://www.ncbi.nlm.nih.gov/pubmed/19085447 | Study Design
1012 | Zerva A, Nassis GP, Krekoukia M, Psarra G, Sidossis LS. Effect of eating frequency on body composition in 9-11year-old children. Int J Sports Med. 2007. 28:265–70 https://www.ncbi.nlm.nih.gov/pubmed/17024645 | Study Design
1013 | Zhang L, Cordeiro LS, Liu J, Ma Y. The Association between Breakfast Skipping and Body Weight, Nutrient Intake, and Metabolic Measures among Participants with Metabolic Syndrome. Nutrients. 2017;9(4). https://www.ncbi.nlm.nih.gov/pubmed/28420112. | Daily Eating Occasions Not Reported
1014 | Zhu Y, Hollis JH. Associations between eating frequency and energy intake, energy density, diet quality and body weight status in adults from the USA. Br J Nutr. 2016. 115:2138–44 https://www.ncbi.nlm.nih.gov/pubmed/27109636 | Eating Frequency Data Collection
1015 | Ziaee V, Kihanidoost Z, Younesian M, Akhavirad M, Bateni F, Kazemianfar Z, Hantoushzadeh S. The effect of Ramadan fasting on outcome of pregnancy. Iranian Journal of Pediatrics. 2010. 20:181–186 http://search.ebscohost.com/login.aspx?direct=true&db=jlh&AN=105055693&site=ehost-live | Daily Eating Occasions Not Reported
1016 | Ziaee V, Razaei M, Ahmadinejad Z, Shaikh H, Yousefi R, Yarmohammadi L, Bozorgi F, Behjati MJ. The changes of metabolic profile and weight during Ramadan fasting. Singapore Med J. 2006. 47:409–14 https://www.ncbi.nlm.nih.gov/pubmed/16645692 | Intervention/Exposure, Daily Eating Occasions Not Reported
1017 | Zimmerman AR, Ferriday D, Davies SR, Martin AA, Rogers PJ, Mason A, Brunstrom JM. What time is my next meal? delay-discounting individuals choose smaller portions under conditions of uncertainty. Appetite. 2017. 116:284–290 https://www.ncbi.nlm.nih.gov/pubmed/28501421 | Intervention/Exposure, Daily Eating Occasions Not Reported
1018 | Zimmerman AR, Johnson L, Brunstrom JM. Assessing chaotic eating using self-report and the UK Adult National Diet and Nutrition Survey: No association between BMI and variability in meal or snack timings. Physiol Behav. 2018. 192:64–71 https://www.ncbi.nlm.nih.gov/pubmed/29580954 | Study Design
1019 | Zoladz JA, Konturek SJ, Duda K, Majerczak J, Sliwowski Z, Grandys M, Bielanski W. Effect of moderate incremental exercise, performed in fed and fasted state on cardio-respiratory variables and leptin and ghrelin concentrations in young healthy men. J Physiol Pharmacol. 2005. 56:63–85 https://www.ncbi.nlm.nih.gov/pubmed/15795476 | Intervention/Exposure
1020 | Zulet MA, Bondia-Pons I, Abete I, de la Iglesia R, Lopez-Legarrea P, Forga L, Navas-Carretero S, Martinez JA. The reduction of the metabolyc syndrome in Navarra-Spain (RESMENA-S) study: a multidisciplinary strategy based on chrononutrition and nutritional education, together with dietetic and psychological control. Nutr Hosp. 2011. 26:16–26 https://www.ncbi.nlm.nih.gov/pubmed/21519726 | Study Design
1021 | Zuo L, He F, Tinsley GM, Pannell BK, Ward E, Arciero PJ. Comparison of High-Protein, Intermittent Fasting Low-Calorie Diet and Heart Healthy Diet for Vascular Health of the Obese. Front Physiol. 2016. 7:350 https://www.ncbi.nlm.nih.gov/pubmed/27621707 | Study Design

v Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

vi In order to determine the inclusion exclusion criteria for country, the Human Development classification was used. This classification is based on the Human Development Index (HDI) ranking from the year the study intervention occurred or data were collected (UN Development Program. HDI 1990-2017 HDRO calculations based on data from UNDESA (2017a), UNESCO Institute for Statistics (2018), United Nations Statistics Division (2018b), World Bank (2018b), Barro and Lee (2016) and IMF (2018). Available from: http://hdr.undp.org/en/data). If the study did not report the year in which the intervention occurred or data were collected, the HDI classification for the year of publication was applied. HDI values are available from 1980, and then from 1990 to present. If a study was conducted prior to 1990, the HDI classification from 1990 was applied. If a study was conducted in 2018 or 2019, the most current HDI classification was applied. When a country was not included in the HDI ranking, the current country classification from the World Bank was used instead ( The World Bank. World Bank country and lending groups. Available from: https://datahelpdesk.worldbank.org/knowledgebase/articles/906519-world-country-and-lending-groups)