# WHAT IS THE RELATIONSHIP BETWEEN THE FREQUENCY OF EATING AND TYPE 2 DIABETES?

## PLAIN LANGUAGE SUMMARY

### What is the question?

- The question is: What is the relationship between the frequency of eating and type 2 diabetes?

### What is the answer to the question?

- Insufficient evidence is available to determine the relationship between the frequency of eating and type 2 diabetes.

### Why was this question asked?

- This important public health question was identified by the U.S. Departments of Agriculture (USDA) and Health and Human Services (HHS) to be examined by the 2020 Dietary Guidelines Advisory Committee.

### How was this question answered?

- The 2020 Dietary Guidelines Advisory Committee, Frequency of Eating Subcommittee conducted a systematic review to answer this question with support from the Nutrition Evidence Systematic Review (NESR) team.
- Frequency of eating was defined as the number of daily eating occasions.

### What is the population of interest?

- The population of interest was generally healthy children through older adults (ages 2 years and older).

### What evidence was found?

- This review included 2 articles that met the inclusion criteria.
- Inconsistent results from 2 prospective cohort studies with critical limitations, were insufficient to draw conclusions.

### How up-to-date is this systematic review?

- This review searched for studies from January, 2000 to September, 2019.

## FULL REVIEW

### Systematic review question

What is the relationship between the frequency of eating and type 2 diabetes?

### Conclusion statement and grade

Insufficient evidence is available to determine the relationship between the frequency of eating and type 2 diabetes. (Grade: Grade not assignable)

### Summary of the evidence

- This systematic review was undertaken to examine the relationship between the frequency of eating and type 2 diabetes.
- This review included 2 prospective cohort studies published between January 2000 and September 2019 that met the inclusion criteria.^1,2^
  ○ One included study reported that adult men who reported 1 to 2 eating occasions per day had a higher risk of type 2 diabetes compared to men who reported 3 eating occasions after 16 years of follow-up.
  ○ One included study did not report an association between frequency of eating in adult women and risk of type 2 diabetes after a 6-year followup.
- Critical limitations were identified within the body of evidence:
  ○ Habitual eating frequency was measured only at baseline, leading to concern that changes in exposure status may have occurred over the follow-up time periods.
  ○ Weak study designs were used to explore this question.
  ○ Beverages and water were not included in assessments of eating occasions.
  ○ The amount of attrition was unknown.
- Due to a small, inconsistent body of evidence with critical limitations, the Committee determined that the evidence was insufficient to draw conclusions about the relationship between frequency of eating and type 2 diabetes.

### Description of the evidence

This systematic review included 2 articles that examined the relationship between the frequency of eating and type 2 diabetes, published between January 2000 and September 2019.^1,2^ Detailed information about the studies are shown in Table 1. Both studies were prospective cohort studies conducted in the United States. One used data from the Health Professionals Follow-up Study^2^ and one used data from the Nurses’ Health Study.^1^

Both studies were conducted in adults, one in an all-male, majority White population with an average age of 58 years^2^ and the other study was an all-female population with an average age of 66 years.^1^ Average BMI was ~26 kg/m^2^ and 25 kg/m^2^ and average habitual intake was 4 and 3 eating occasions per day, respectively.^1,2^

Both studies assessed the relationship between the frequency of eating occasions and the risk of being diagnosed with type 2 diabetes.

### Evidence synthesis

Mekary et al^2^ reported an inverse association in men (mean age of 58 years) between frequency of eating and risk of type 2 diabetes over a 16-year follow-up. Men reporting 1-2 eating occasions per day had a higher risk of type 2 diabetes compared to men with 3 eating occasions per day. Eating 4 or 5-8 times per day compared to 3 eating occasions per day was not associated with risk of type 2 diabetes. Mekary et al^1^ did not report an association in women (mean age 66 years) between eating frequency and risk of type 2 diabetes after a 6-year follow-up. Results are shown in Table 1.

Both included studies had several limitations (Table 2). Both included studies had unknown attrition rates and did not account for missing data or loss to follow-up. In addition, while habitual eating frequency was assessed using validated methods, it was only assessed once at baseline, leading to concerns that changes in exposure status could have occurred over the study follow-ups. Both studies used food frequency questionnaires with an added question to assess frequency of eating; however, the questions used to assess eating occasions were dissimilar between the two studies. In Mekary et al,^2^ participants were asked to indicate whether they ate at different times of the day anchored by meals (before breakfast, breakfast, between breakfast and lunch, lunch, between lunch and dinner, dinner, between dinner and bedtime, or after going to bed). This assessment was focused on eating and beverages were likely not considered. Additionally, the data were collected in 1992 and may not be applicable to the current U.S. population and food supply. In Mekary et al,^1^ participants were asked to indicate, “How many times per day do you eat? Include meals and snacks”. Juice and non-diet soda could be considered an eating occasion, but coffee and diet soda were excluded from this assessment. Neither study explicitly mentioned the consideration of water within the analyses. The differences in these methods made it difficult to compare results from the two studies.

The 2 studies included in this systematic review were designed to examine the relationship between the frequency of eating and type 2 diabetes, and were generalizable to the U.S. population. However, they used different definitions regarding frequency of eating and the reported results. In addition, the included studies had a number of critical risks of bias due to their design and conduct. Publication bias is a concern with this body of evidence given that there were few studies and only one study reported a significant association. Therefore, the evidence was insufficient to be able to draw conclusions about the relationship between the frequency of eating and type 2 diabetes.

### Research recommendations

- More controlled trials are needed that assess the frequency of eating and various outcomes.
- Future studies should develop a consistent definition of an ingestive event that includes eating and drinking and methods to quantify it.
- Future studies should document the frequency of water consumption.
- In future studies, collection of ingestive frequency data should:
  ○ Report number of ingestive events across 24 hours.
  ○ Collect a minimum of 3 days of ingestive event data on at least 2 discrete occasions to allow assessment of estimate reliability.
- Future studies should report information on food insecurity in relation to frequency of eating to allow isolation of voluntary versus involuntary eating frequency effects.
- Future research should report key confounders and other factors to be considered, such as:
  ○ Sex, Age, Race/ethnicity, Habitual eating frequency, Smoking, Anthropometry, Socioeconomic status, Physical activity, Cultural practices, Total energy intake, Diet energy density, Energy state of the diet (restriction/surplus), Energy balance (total energy intake/total energy expenditure), Chrononutrition factors (time of day, (consistency of) habitual eating frequency, and duration between ingestive events and/or ingestive periods), Portion size, Macronutrient content, Location of eating occasion, Eating environment (who you eat with, work/school/exercise schedule), Holiday eating (seasonal), Sleep schedule (shift work), Secondary eating, Dentition, Hydration status, Pregnancy status, Pubertal status, Menopausal status, Biochemical changes

### Included articles

1 Mekary RA, Giovannucci E, Cahill L, Willett WC, van Dam RM, Hu FB. Eating patterns and type 2 diabetes risk in older women: breakfast consumption and eating frequency. Am J Clin Nutr. 2013;98(2):436–443.doi:10.3945/ajcn.112.057521 23761483
2 Mekary RA, Giovannucci E, Willett WC, van Dam RM, Hu FB. Eating patterns and type 2 diabetes risk in men: breakfast omission, eating frequency, and snacking. Am J Clin Nutr. 2012;95(5):1182–1189.doi: 10.3945/ajcn.111.028209 22456660

Table 1 Description of studies included in the systematic review to examine the relationship between frequency of eating and type 2 diabetes^ii^

Study and population characteristics | Intervention/Exposure, Comparator and Outcome(s) | Results | Key Confounders and Study Limitations
Mekary, 2012 ^2^; Prospective Cohort Study, Health Professionals Follow-Up Study, United States; Analytic N=29206; Participant characteristics:; - Age: ~58y, SE=9; - Sex: 0% female; - Race/Ethnicity: 97% White; - Habitual eating frequency: ~3 EOs/d; 82% eat breakfast; - Smoking: 7% current smokers; - Anthropometry: BMI ~25 kg/m^2^; - Physical activity: ~37 MET/-h/wk; - Total energy intake: ~2000 kcal/d; - Alcohol intake: ~10.5 g/d; - Family history of T2D: 13%; Excluded from study or analysis: Females; Did not complete the baseline FFQ, had implausible energy intakes (>4200 or <800 kcal/d), had left >70 food items blank, or did not answer the meal-frequency questions, diagnosed with diabetes, cardiovascular disease, and cancer (except for nonmelanoma skin cancer) | Exposure of interest: Frequency of EOs: 1-2, 3, 4, 5-8 times per day; [underlined: Assessment method and timing]: FFQ, collected in 1992; indicate eating before breakfast, breakfast, between breakfast and lunch, lunch, between lunch and dinner, dinner, between dinner and bedtime, or after going to bed (question focused on eating, so likely beverages were not considered); [underlined: Treatment of beverages]: Likely not included; Outcomes and assessment methods:; Type 2 diabetes: Self-reported, confirmed using the National Diabetes Data Group criteria; every 2y for 16y | T2D after 16y:; - 1-2 times/d (n=254): RR: 1.25, 95% CI: 1.08, 1.45; - 3 times/d (n=835): RR: 1.00; - 4 times/d (n=714): RR: 1.09, 95% CI: 0.99, 1.21 (NS after BMI adjustment); - 5-8 times/d (n=141): RR: 0.90, 95% CI: 0.75, 1.09; - p-trend = 0.04; Results became NS when other covariates were added to the model, such as breakfast consumption (P-trend = 0.36) or coffee intake (P-trend = 0.39); Results were similar when stratified by breakfast consumption (yes/no).; Summary: Men who ate 1–2 times/d at 58y also had a higher risk of T2D than did men consumed 3 meals/d after 16y f/u. Eating 4 or 5-8 times were not associated with risk of T2D. | Model Adjustments:; - Key confounders: age, sex, race/ethnicity, physical activity, smoking, anthropometry; - Other factors to be considered: family history of T2D, energy intake; - Other: alcohol intake, cereal fiber intake, prudent dietary pattern Western dietary pattern; TEI adjusted: Yes; Limitations:; - Selection criteria related to FoE T2D; - FoE data only assessed at baseline with a 16y f/u leading to a concern that changes in exposure status occurred over f/u; - FoE assessment method not validated; - High attrition rate; - Beverages and water were not mentioned in FoE assessment; - FoE data collection from 1992 and may not be applicable to current populations and food supply; Funding sources: NIH
Mekary, 2013 ^1^; Prospective Cohort Study, Nurses’ Health Study, United States; Analytic N=46289; Participant characteristics:; - Age: ~66y, SE=7; - Sex: 100% female; - Race/Ethnicity: NR; - Habitual eating frequency: ~4 EOs/d; 77% breakfast consumers; - Smoking: 8% current smokers; - Anthropometry: BMI ~26 kg/m^2^; - Physical activity: ~18 MET/-h/wk; - Total energy intake: ~1700 kcal/d; - Family Hx of diabetes: 23%; - Postmenopausal hormone users: ~42%; - Alcohol intake: ~6 g/d; Excluded from study or analysis: Not a registered nurse; males, age <30 or >55 y at baseline; did not complete the baseline FFQ, had implausible energy intakes (>3500 or <500 kcal/d), did not answer the mealfrequency questions, diagnosed with diabetes, cardiovascular disease, and cancer (except for nonmelanoma skin cancer) | Exposure of interest: Frequency of EOs: 1-2, 3, 4-5, >6 times per day; [underlined: Assessment method and timing]: FFQ, collected in 2002; indicate eating times/day using question, “How many times per day do you eat? Include meals and snacks.” (for snacks, including juice and non-diet soda, but excluding coffee and diet soda); [underlined: Treatment of beverages]: Excluded coffee and diet soda from assessment; water and other noncaloric beverages were not mentioned; Outcomes and assessment methods:; - Type 2 diabetes: Self-reported, confirmed using an additional questionnaire and the American Diabetes Association criteria; every 2y for 6y | T2D after 6y:; - 1-2 times/d (n=11058): RR: 1.13, 95% CI: 0.87, 1.46; - 3 times/d (n=69373): RR: 1.00; - 4-5 times/d (n=984): RR: 1.04, 95% CI: 0.92, 1.17; - >6 times/d (n=139): RR: 0.89, 95% CI: 0.73, 1.08; - p-trend = 0.15; Results were similar when stratified by breakfast consumption (yes/no).; Summary: Frequency of eating in women at age 66y was not significantly associated with risk of T2D after 6y f/u. | Model Adjustments for T2D:; - Key confounders: age, sex, physical activity, smoking, anthropometry; - Other factors to be considered: family history of T2D, energy intake, menopausal status and hormone use; - Other: alcohol intake, cereal fiber intake, Alternative Healthy Eating Index 2010; TEI adjusted: Yes; Limitations:; - Race/ethnicity not accounted for in T2D analyses FoE assessment method not validated; - FoE data only assessed at baseline with a 6y f/u leading to a concern that changes in exposure status occurred over f/u; - High attrition rate; - Water and beverages other than juice and non-diet soda were not assessed or accounted for in FoE assessment; Funding sources: NIH

Table 2 Risk of bias for observational studies examining the frequency of eating and type 2 diabetes^iii,iv^

| Confounding | Selection of participants | Classification of exposures | Deviations from intended exposures | Missing data | Outcome measurement | Selection of the reported result
Mekary, 2012 ^2^ | Moderate | Serious | Serious | Critical | Serious | Moderate | Moderate
Mekary, 2013 ^1^ | Serious | Serious | Serious | Critical | Moderate | Moderate | Moderate

ii Abbreviations: CI – confidence interval; d – day(s); EO – eating occasion; FFQ – food frequency questionnaire; FoE – frequency of eating; f/u – follow-up; MET - metabolic equivalent of task; NR – not reported; NS – not significant; RR – risk ratio; SE – standard error; SES – socioeconomic status; T2D – type 2 diabetes; TEI – total energy intake; wk – week(s); y – year(s)

iii A detailed description of the methodology used for assessing risk of bias is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

iv Possible ratings of low, moderate, serious, critical, or no information determined using the “Risk of Bias for Nutrition Observational Studies” tool (RoB-NObs) ( Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC. )