# List of abbreviations

Abbreviation: Full name
CHD: Coronary heart disease
CNPP: Center for Nutrition Policy and Promotion
CVD: Cardiovascular disease
DPS: Division of Prevention Science
FFQ: Food frequency questionnaire
F/U: Follow-up
FNS: Food and Nutrition Service
FoE: Frequency of eating
HHS: United States Department of Health and Human Services
NESR: Nutrition Evidence Systematic Review
NIH: National Institute of Health
ODPHP: Office of Disease Prevention and Health Promotion
ONGA: Office of Nutrition Guidance and Analysis
USDA: United States Department of Agriculture