# WHAT IS THE RELATIONSHIP BETWEEN THE FREQUENCY OF EATING AND RISK OF CARDIOVASCULAR DISEASE?

## PLAIN LANGUAGE SUMMARY

### What is the question?

- The question is: What is the relationship between the frequency of eating and risk of cardiovascular disease?

### What is the answer to the question?

- Insufficient evidence is available to determine the relationship between the frequency of eating and cardiovascular disease.

### Why was this question asked?

- This important public health question was identified by the U.S. Departments of Agriculture (USDA) and Health and Human Services (HHS) to be examined by the 2020 Dietary Guidelines Advisory Committee.

### How was this question answered?

- The 2020 Dietary Guidelines Advisory Committee, Frequency of Eating Subcommittee conducted a systematic review to answer this question with support from the Nutrition Evidence Systematic Review (NESR) team.
- Frequency of eating was defined as the number of daily eating occasions.

### What is the population of interest?

- The population of interest was generally healthy children through older adults (ages 2 and older).

### What evidence was found?

- This review identified 2 articles that met the inclusion criteria.
- Inconsistent results from 2 prospective cohort studies with critical limitations, were insufficient to draw conclusions.

### How up-to-date is this systematic review?

- This review searched for studies from January 2000 to September 2019.

## FULL REVIEW

### Systematic review question

What is the relationship between the frequency of eating and risk of cardiovascular disease?

### Conclusion statement and grade

Insufficient evidence is available to determine the relationship between the frequency of eating and cardiovascular disease. (Grade: Grade not assignable)

### Summary of the evidence

- This systematic review was undertaken to examine the relationship between the frequency of eating and cardiovascular disease.
- This review identified 2 prospective cohort studies published between January, 2000 and September, 2019 that met the inclusion criteria for this systematic review.^1,2^
- The studies were inconsistent in terms of how they defined and examined frequency of eating, the outcomes they examined, and in their reported results:
  ○ One included study reported that a higher eating frequency at baseline was associated with lower blood pressure after a 5-year follow-up.
  ○ One included study reported no association between eating frequency at baseline and risk of coronary heart disease after a 16-year follow-up.
- Critical limitations were identified within the body of evidence:
  ○ Weak study designs were used to explore this question.
  ○ Eating frequency was measured only at baseline, leading to concern that changes in exposure status may have occurred over the follow-up time periods.
  ○ The amount of attrition was unknown.
  ○ The study showed several risks of bias.
  ○ Inconsistent outcomes were included across studies with respect to relative risks and 95% confidence intervals for CHD, systolic blood pressure, diastolic blood pressure, and hypertension.
  ○ Water consumption was not explicitly mentioned in either included study.
- Due to the small body of evidence with inconsistency in design and reported results and several limitations, the Committee determined that the evidence was insufficient to draw conclusions about the relationship between frequency of eating and cardiovascular disease.

### Description of the evidence

This systematic review included 2 articles that addressed the relationship between the frequency of eating and cardiovascular disease, published between January 2000 and September 2019.^1,2^ Basic characteristics of the studies are shown in Table 1. The studies were both prospective cohort studies. One used data from the Health Professionals Follow-up Study conducted in the United States and one was conducted in Greece.

Both studies were conducted in adults, one in an all-male, majority White population with an mean age of 58 years^1^ and the other study was 45% female with an average age of 47.8 years in a Greek population.^2^ Average BMI was about 25 and 26 kg/m^2^ and average habitual intakes were 3.5 and 5 eating occasions per day, respectively.^1,2^

In Cahill et al,^1^ the authors looked at the frequency of eating occasions at baseline in relation to risk of coronary heart disease over a 16-year follow-up. In Karatzi et al,^2^ the authors assessed the relationship between frequency of eating occasions at baseline and systolic blood pressure, diastolic blood pressure, and risk of hypertension after 5 years of follow-up.

### Evidence synthesis

Cahill et al^1^ reported no association in males with a mean age of 58 years, between frequency of eating at baseline and risk of coronary heart disease over a 16-year follow-up. Karatzi et al^2^ reported an inverse association in adults between eating frequency at baseline and systolic and diastolic blood pressure changes, and risk of hypertension after a 5-year follow-up. Results are shown in Table 1.

Both included studies had several limitations (Table 2). Both included studies had unknown attrition rates and did not account for missing data or loss to follow-up. In addition, while habitual eating frequency was assessed, it was only assessed once at baseline, leading to concerns that changes in exposure status could have occurred over the study follow-ups. Data collection methods assessing frequency of eating and the definitions used for eating occasions were inconsistent between the two studies. Cahill et al^1^ added a question to a food frequency questionnaire (FFQ) in which participants were asked to indicate if they ate at different times of the day anchored by meals (before breakfast, breakfast, between breakfast and lunch, lunch, between lunch and dinner, dinner, between dinner and bedtime, or after going to bed). This method was focused on eating and beverages were likely not considered in this assessment method. Karatzi et al^2^ used a 3-day dietary record and defined an eating occasion as any time when food or beverages were consumed at least 15 minutes apart. Neither study explicitly mentioned the consideration of water within the analyses. The differences in these methods made it difficult to compare results from the studies.

The 2 studies included in this systematic review were designed to examine the relationship between frequency of eating and cardiovascular disease, and were generalizable to the U.S. population. However, they were inconsistent in their definitions and examination of frequency of eating, the outcomes considered, and the reported results. In addition, the included studies had multiple critical risks of bias due to their design and conduct. Publication bias is a concern with this body of evidence given that there were few studies and only one study reported a significant association. Therefore, the evidence was insufficient to be able to draw conclusions about the relationship between the frequency of eating and cardiovascular disease.

### Research recommendations

- More controlled trials are needed that assess the frequency of eating and various outcomes.
- Future studies should develop a consistent definition of an ingestive event that includes eating and drinking and methods to quantify it.
- Future studies should document the frequency of water consumption.
- In future studies, collection of ingestive frequency data should:
  ○ Report number of ingestive events across 24 hours.
  ○ Collect a minimum of 3 days of ingestive event data on at least 2 discrete occasions to allow assessment of estimate reliability.
- Future studies should report information on food insecurity in relation to frequency of eating to allow isolation of voluntary versus involuntary eating frequency effects.
- Future research should report key confounders and other factors to be considered, such as:
  ○ Sex, Age, Race/ethnicity, Habitual eating frequency, Smoking, Anthropometry
  ○ Socioeconomic status, Physical activity, Cultural practices, Total energy intake, Diet energy density, Energy state of the diet (restriction/surplus), Energy balance (total energy intake/total energy expenditure), Chrononutrition factors (time of day, (consistency of) habitual eating frequency, and duration between ingestive events and/or ingestive periods), Portion size, Macronutrient content, Location of eating occasion, Eating environment (who you eat with, work/school/exercise schedule), Holiday eating (seasonal), Sleep schedule (shift work), Secondary eating, Dentition, Hydration status, Pregnancy status, Pubertal status, Menopausal status, Biochemical changes

### Included articles

1 Cahill LE, Chiuve SE, Mekary RA, . Prospective study of breakfast eating and incident coronary heart disease in a cohort of male US health professionals. Circulation. 2013;128(4):337–343. doi:10.1161/circulationaha.113.001474 23877060
2 Karatzi K, Georgiopoulos G, Yannakoulia M, . Eating frequency predicts new onset hypertension and the rate of progression of blood pressure, arterial stiffness, and wave reflections. J Hypertens. 2016;34(3):429–437. doi:10.1097/hjh.0000000000000822 26771340

Table 1

Description of studies included in the systematic review to examine the relationship between frequency of eating and cardiovascular disease.^ii^

Study and population characteristics | Exposure, Comparator and Outcome(s) | Results | Key Confounders and Study Limitations
Cahill, 2013^1^; Prospective Cohort Study, Health Professionals Follow-Up Study, United States; Analytic N=26902; Participant characteristics:; [underlined: Key Confounders:]; - Age: ~58y (46-81y); - Sex: 0% female; - Race/Ethnicity: 97% White; - Habitual eating frequency: ~3.5 EOs/d, ~87% breakfast consumers; - Smoking: 7% current smokers; - Anthropometry: ~25kg/m^2^; [underlined: Reported Other Factors to be Considered:]; - SES: Married ~90%; - Physical activity: ~37 MET/-h/wk, ~11% watch >21h tv/wk; - Sleep: <7hr/24h ~16%; - Drink alcohol ~76%; - Total energy intake: ~1950 kcal/d; - Health: diabetes ~4%; hypertension ~26%; hypercholesterolemia ~34%; [underlined: Excluded from selection into study or analysis]: Females, did not complete the baseline FFQ, had implausible energy intakes (>4200 or <800 kcal/d), had left >70 food items blank, or did not answer the meal-frequency questions, diagnosed with diabetes, cardiovascular disease, and cancer (except for nonmelanoma skin cancer) | Exposure of interest:; Frequency of eating occasions: 1-2, 3, 4-5, ≥6 times per day; [underlined: Assessment method and timing]: FFQ, collected in 1992; indicate eating before breakfast, breakfast, between breakfast and lunch, lunch, between lunch and dinner, dinner, between dinner and bedtime, or after going to bed (question focused on eating, so likely beverages were not considered); [underlined: Treatment of beverages]: Likely not included; Outcomes and assessment methods:; Coronary Heart Disease (CHD): Non-fatal myocardial infarction or fatal CHD were self-reported and confirmed based on medical record review; every 2y for 16y | TEI adjusted: Yes; CHD:; - 1-2 times/d (n=150): RR: 1.08, 95% CI: 0.90, 1.29; - 3 times/d (n=728): RR: 1.00; - 4-5 times/d (n=611): RR: 1.00, 95% CI: 0.89, 1.11; - ≥6 times/d (n=38): RR: 1.14, 95% CI: 0.81, 1.61; - p-trend = NS; Summary: Frequency of eating at men with a mean age 58y was not significantly associated with risk of CHD after 16y f/u. | Model Adjustments:; - Key confounders: age, sex, race/ethnicity, physical activity, smoking, anthropometry; - Other factors to be considered: SES, family history of MI, energy intake, sleep; - Other: alcohol intake, diet quality, marital status, physical exam in last 2y, television watching, diagnosis with diabetes, hypertension, or hypercholesterolemia, breakfast, late night eating, stress, antidepressant medication, daily number of cigarettes among smokers, bodyweight change and specific dietary components such as folate, whole grains, fiber or saturated fat; Limitations:; - Selection criteria likely related to FoE and CVD; - FoE data only assessed at baseline with a 16y f/u leading to a concern that changes in exposure status occurred over f/u; - FoE assessment method not validated; - High attrition rate; - Beverages and water was not mentioned in FoE assessment; - FoE data collection from 1992 and may not be applicable to current populations and food supply; Funding sources: NIH, Canadian Institutes of Health Research
Karatzi, 2016^2^; Prospective Cohort Study, Greece; Analytic N=115; Participant characteristics:; [underlined: Key Confounders:]; - Age: 47.8y; - Sex: 45% female; - Race/Ethnicity: NR; - Habitual eating frequency, median, IQR: 15, 13-18 EOs/3d; - Smoking: 40%; - Anthropometry: BMI: 26.2kg/m^2^; waist circumference: 89.5 cm; hip circumference: 102 cm; waist to hip ratio: 0.854; [underlined: Reported Other Factors to be Considered:]; - Total energy intake: ~1823kcal; - Macronutrient content: carbohydrate energy ~39.8%; Lipid energy ~41.3%; protein energy ~38.2%;; [underlined: Excluded from selection into study or analysis]: history of coronary artery disease, diabetes, liver or endocrine diseases, autoimmune disease, cancer, or active infection; alcohol consumption ≥30g/d; dieting at baseline | Exposure of interest:; Frequency of EOs: 1-5, ≥6 per day; [underlined: Assessment method and timing]: 3d food records on 2 consecutive weekdays and 1 weekend day at baseline; eating frequency: number of EOs/d (mean of 3 d assessments); EO: any EO when food or drink was consumed at least 15 min apart (may include alcohol, soft drinks, kcal-free meals, or coffees and teas eaten in the absence of food.; [underlined: Treatment of non-caloric beverages:] Included as an EO although water not mentioned.; Outcomes and assessment methods:; Cardiovascular disease: Blood pressure was measured (average of 2 measures, 1 min apart), at baseline and 5y follow-up; Hypertension was defined as systolic blood pressure >140mmHg and/or diastolic blood pressure > 90mmHg. Participants fasted for 12 h and abstained from alcohol, caffeine, and smoking for 1 d before assessment at lab. | TEI adjusted: Yes; CVD:; - SBP: HR 0.366, p=0.05; - DBP: 0.452, p=0.02; - Hypertension: HR 5.4, p=0.004; Summary: Higher eating frequency at baseline was associated with lower systolic blood pressure and diastolic blood pressure changes, and decreased risk of hypertension after a 5-year follow-up. | Model Adjustments:; - Key confounders: age, sex, smoking, BMI; - Other factors to be considered: total energy intake; - Other: HDL, HR, HOMA; Limitations:; - Race/ethnicity (study took place in Greece) was not accounted for in the analysis; - Selection criteria likely related to FoE and CVD; - FoE data only assessed at baseline with a 5y f/u leading to a concern that changes in exposure status occurred over f/u; - High attrition rate; - Water not mentioned in data collection; Funding sources: NR

Table 2

Risk of bias for observational studies examining the frequency of eating and cardiovascular disease^iii,iv^

| Confounding | Selection of participants | Classification of exposures | Deviations from intended exposures | Missing data | Outcome measurement | Selection of the reported result
Cahill, 2013^1^ | Moderate | Serious | Serious | Critical | Moderate | Moderate | Moderate
Karatzi, 2016^2^ | Moderate | Serious | Serious | Critical | Low | Moderate | Serious

ii Abbreviations: CHD – coronary heart disease; CVD – cardiovascular disease; d – day; DBP – diastolic blood pressure; EO – eating occasion; f/u – follow-up; FoE – frequency of eating; h – hour; HDL – high-density lipoprotein, HOMA – Homeostatic Model Assessment of Insulin Resistance; HR – hazard ratio; NS – not significant; NR – not reported; SBP – systolic blood pressure; SD – standard deviation; SE – standard error; SES – socioeconomic status; TEI – total energy intake, y – year

iii A detailed description of the methodology used for assessing risk of bias is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

iv Possible ratings of low, moderate, serious, critical, or no information determined using the “Risk of Bias for Nutrition Observational Studies” tool (RoB-NObs)( Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC. )