# List of abbreviations

Abbreviation: Full name
AMDR: Acceptable macronutrient distribution range
DQI-I: Diet quality index - international
EWGSOP: European Working Group on Sarcopenia in Older Adults
HHS: United States Department of Health and Human Services
mHDI: Modified Healthy Diet Indicator
MDS: Mediterranean diet score
NESR: Nutrition Evidence Systematic Review
ONGA: Office of Nutrition Guidance and Analysis
PCS: Prospective cohort study
SES: Socioeconomic status
USDA: United States Department of Agriculture