# METHODOLOGY

The NESR team used its rigorous, protocol-driven methodology to support the 2020 Dietary Guidelines Advisory Committee in conducting this systematic review.

NESR’s systematic review methodology involves:

- Developing a protocol,
- Searching for and selecting studies,
- Extracting data from and assessing the risk of bias of each included study,
- Synthesizing the evidence,
- Developing conclusion statements,
- Grading the evidence underlying the conclusion statements, and
- Recommending future research.

A detailed description of the methodology used in conducting this systematic review is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews, and can be found in the 2020 Dietary Guidelines Advisory Committee Report, Part C: Methodology.^xi^ This systematic review was peer reviewed by Federal scientists, and information about the peer review process can also be found in the Committee’s Report, Part C: Methodology. Additional information about this systematic review, including a description of and rationale for any modifications made to the protocol can be found in the 2020 Dietary Guidelines Advisory Committee Report, Chapter 8. Dietary Patterns.

Below are details of the final protocol for the systematic review described herein, including the:

- Analytic framework
- Literature search and screening plan
- Literature search and screening results

## ANALYTIC FRAMEWORK

The analytic framework (Figure 1) illustrates the overall scope of the systematic review, including the population, the interventions and/or exposures, comparators, and outcomes of interest. It also includes definitions of key terms and identifies key confounders and other factors considered in the systematic review. The inclusion and exclusion criteria that follow provide additional information about how parts of the analytic framework were defined and operationalized for the review.

Figure 1 Analytic framework

An analytic framework visually represents the overall scope of the systematic review question, and depicts the contributing elements that were examined and evaluated, including the target population, exposure, comparison, outcomes, and key confounders. This is the analytic framework for the systematic review question on dietary patterns consumed and sarcopenia. For this systematic review, the target population for the intervention/exposure considered was adolescents through older adults, who are healthy and/or at risk of chronic disease. The target population for the outcomes considered was adults through older adults. The interventions or exposures considered were consumption of and/or adherence to a dietary pattern and their comparators were consumption of and/or adherence to a different dietary pattern or different levels of consumption of and/or adherence to a dietary pattern. The outcomes considered include sarcopenia or severe sarcopenia. The key confounders are sex, age, race/ethnicity, socioeconomic status, anthropometry, dietary protein intake, physical activity, and physical disability (e.g., wheelchair, frailty, immobility). The other factors to be considered are total energy intake, malnutrition, vitamin D status, depression, malabsorption, neurodegenerative disease, equilibrium disorders, osteoporosis, and endocrine factors (e.g., type 2 diabetes, corticosteroids, thyroid disease).

## LITERATURE SEARCH AND SCREENING PLAN

### Inclusion and exclusion criteria

This table provides the inclusion and exclusion criteria for the systematic review. The inclusion and exclusion criteria are a set of characteristics used to determine which articles identified in the literature search were included in or excluded from the systematic review.

Table 4 Inclusion and exclusion criteria

Category | Inclusion Criteria | Exclusion Criteria
Study design | - Randomized controlled trials; - Non-randomized controlled trials, including quasi-experimental and controlled before and after studies; - Prospective cohort studies; - Retrospective cohort studies; - Nested case-control studies | - Uncontrolled trials; - Case-control studies; - Cross-sectional studies; - Uncontrolled before-and-after studies; - Narrative reviews; - Systematic reviews; - Meta-analyses
Intervention/exposure | - Studies that examine consumption of and/or adherence to a; 1 Dietary pattern [i.e., the quantities, proportions, variety, or combination of different foods, drinks, and nutrients (when available) in diets, and the frequency with which they are habitually consumed]), including, at a minimum, a description of the foods and beverages in the pattern; ○ Dietary patterns may be measured or derived using a variety of approaches, such as adherence to a priori patterns (indices/scores), data driven patterns (factor or cluster analysis), reduced rank regression, or other methods, including clinical trials; and/or | - Studies that; 1a do not provide a description of the dietary pattern, which at minimum, must include the foods and beverages in the pattern (i.e., studies that examine a labeled dietary patterns, but do not describe the foods and beverages consumed)
| 2 Diet based on macronutrient distribution outside of the AMDR and; ○ include the macronutrient distribution of carbohydrate, fat, and protein of the diet, and; ○ include at least one macronutrient outside of the acceptable macronutrient distribution range (AMDR)^xii,^ ^xiii^ | 2a Examine consumption of and/or adherence to a diet based on macronutrient proportion in which all macronutrients are within the AMDR.; 2b Do not describe the entire macronutrient distribution of the diet (i.e., studies that only examine a single macronutrient in relation to outcomes)
Comparator | - Dietary patterns described by foods and beverages consumed:; ○ Consumption of and/or adherence to a different dietary pattern; ○ Different levels of consumption of and/or adherence to a dietary pattern; - Diets described by macronutrient distribution; ○ Different macronutrient distribution of carbohydrate, fat, and protein | N/A
Outcomes | Studies that report sarcopenia or severe sarcopenia | N/A
Date of publication | January 2000 – October 2019 | Articles published prior to January 2000 or after October 2019
Publication status | Articles that have been peer-reviewed | Articles that have not been peer-reviewed and are not published in peer-reviewed journals, including unpublished data, manuscripts, pre-prints, reports, abstracts, and conference proceedings
Language of publication | Articles published in English | Articles published in languages other than English
Country ^xiv^ | Studies conducted in countries ranked as high or higher human development | Studies conducted in countries ranked as medium or lower human development
Study participants | - Human participants; - Males; - Females | - Non-human participants (i.e., animals); - Women during pregnancy and lactation
Age of study participants | - Age at intervention or exposure:; ○ Adolescents (ages 12-18 years); ○ Adults (ages 19-64 years); ○ Older adults (ages 65 years and older); - Age at outcome:; ○ Adults (ages 19-64 years); ○ Older adults (ages 65 years and older) | - Age at intervention or exposure:; ○ Infants and toddlers (birth to 24 months); ○ Children (ages 2-12 years); - Age at outcome:; ○ Infants and toddlers (birth to 24 months); ○ Children and adolescents (ages 2-18 years)
Health status of study participants | - Studies that enroll participants who are healthy and/or at risk for chronic disease, including those with obesity; - Studies that enroll some participants diagnosed with a disease or with sarcopenia or severe sarcopenia | - Studies that exclusively enroll participants diagnosed with a disease. (For this criterion, studies that exclusively enroll subjects with obesity will be included.); - Studies that exclusively enroll participants diagnosed with sarcopenia, or severe sarcopenia (i.e., studies that aim to treat participants who have already been diagnosed with the outcome of interest)

### Electronic databases and search terms

Listed below are the databases searched to identify all potentially relevant articles that have been published to address the systematic review question. A search strategy was developed and implemented in three databases (PubMed, Cochrane Central Register of Controlled Trials (CENTRAL), and Embase) to conduct this systematic review.

#### PubMed

- Provider: U.S. National Library of Medicine
- Date(s) Searched: October 8, 2019
- Date range searched: January 1, 2000-October 8, 2019
- Search Terms:
  - #1 - dietary pattern* OR diet pattern* OR eating pattern* OR food pattern* OR diet quality* OR eating habit* OR dietary habit* OR diet habit* OR food habit* OR beverage habit* OR “Feeding Behavior”[Mesh:NoExp] OR dietary profile* OR food profile* OR diet profile* OR eating profile* OR dietary guideline* OR dietary recommendation* OR dietary intake* OR eating style* OR “Diet, Mediterranean”[Mesh] OR Mediterranean Diet*[tiab] OR “Dietary Approaches To Stop Hypertension”[Mesh] OR Dietary Approaches To Stop Hypertension Diet* OR DASH diet* OR “Diet, Gluten-Free”[Mesh] OR Gluten Free diet* OR prudent diet* OR “Diet, Paleolithic”[Mesh] OR Paleolithic Diet* OR “Diet, Vegetarian”[Mesh] OR vegetarian diet*[tiab] OR vegan diet* OR “Diet, Healthy”[Mesh] OR plant based diet* OR “Diet, Western”[Mesh] OR western diet* OR “Diet, Carbohydrate-Restricted”[Mesh] OR low-carbohydrate diet* OR high carbohydrate diet* OR Ketogenic Diet* OR Nordic Diet* OR “Diet, Fat-Restricted”[Mesh] OR “Diet, High-Fat”[Mesh] OR “Diet, High-Protein”[Mesh] OR high protein diet*[tiab] OR protein intake* OR high-fat diet* OR low fat diet* OR “Diet, Protein-Restricted”[Mesh] OR low protein diet* OR “Diet, Sodium-Restricted”[Mesh] OR low-sodium diet* OR low salt diet* OR ((“Dietary Proteins”[Mesh] OR dietary protein*[tiab] OR “Dietary Carbohydrates”[Mesh] OR dietary carbohydrate*[tiab] OR “Dietary Fats”[Mesh] OR dietary fat*[tiab] OR hypocaloric OR hypo-caloric) AND (diet[tiab] OR diets[tiab] OR consumption[tiab] OR intake[tiab] OR supplement*[tiab])) OR ((“Guideline Adherence”[Mesh] OR guideline adherence*)AND (diet[tiab] OR dietary[tiab] OR food[tiab] OR beverage*[tiab] OR nutrition*[tiab])) OR diet score* OR diet quality score* OR diet quality index* OR kidmed OR diet index* OR dietary index* OR food score* OR MedDietScore OR healthy eating index[tiab] OR ((pattern[tiab] OR patterns[tiab] OR consumption[tiab] OR habit*[tiab]) AND (“Diet”[Mesh:NoExp] OR diet[tiab] OR diets[tiab] OR dietary[tiab] OR “Food”[Mesh] OR food[tiab] OR foods[tiab] OR “Beverages”[Mesh] OR beverage[tiab] OR beverages[tiab]))
  - #2 - “Sarcopenia”[Mesh] OR sarcopen* OR presarcopen* OR “Muscular Atrophy”[Mesh:NoExp] OR muscular atroph* OR “Muscle Fatigue”[Mesh] OR muscle fatigue[tiab] OR “Muscle Strength”[Mesh] OR muscle wast* OR muscle weak* OR muscle loss* OR muscle function* OR hand strength* OR grip strength* OR handgrip* OR pinch strength* OR “Physical Functional Performance”[Mesh] OR physical performance* OR “Psychomotor Performance”[Mesh] OR psychomotor performance[tiab] OR ((muscle[tiab] OR muscles[tiab] OR “Muscles”[Mesh] OR “Muscle, Skeletal”[Mesh]) AND (“Fatigue”[Mesh] OR fatigue[tiab] OR weakness[tiab] OR “Frailty”[Mesh] OR frail[tiab] OR frailty[tiab] OR “Geriatric Assessment”[Mesh] OR geriatric*[tiab] OR “Osteoporosis”[Mesh] OR osteoporos*[tiab] OR “Age Factors”[Mesh] OR “Aging”[Mesh] OR “Obesity”[Mesh] OR obesity[tiab] OR “Body Mass Index”[Mesh] OR body mass index[tiab] OR BMI[tiab] OR lean mass[tiab] OR fat mass[tiab] OR “Activities of Daily Living”[Mesh] OR “Quality of Life”[Mesh] OR quality of life[tiab] OR “Postural Balance”[Mesh] OR posture*[tiab] OR “Physical Exertion”[Mesh] OR physical exertion*[tiab] OR “Mobility Limitation”[Mesh] OR mobility limitation* OR “Motor Activity”[Mesh] OR motor activit*[tiab] OR “Walking”[Mesh] OR walking[tiab] OR “Gait”[Mesh] OR gait[tiab])) OR ((“Aging”[Mesh] OR older adult*[tiab]) AND (physical activit*[tiab] OR physical function[tiab] OR physical impairment[tiab] OR physical performance[tiab] OR functional limit*[tiab] OR functional decline[tiab] OR “Mobility Limitation”[Mesh] OR mobility limitation* OR “Walking”[Mesh] OR walking[tiab] OR “Activities of Daily Living”[Mesh] OR activities of daily living[tiab] OR “Independent Living”[Mesh] OR independent living[tiab] OR “Quality of Life”[Mesh] OR quality of life[tiab]))
  - #3 - (#1 AND #2)
  - #4 - (#1 AND #2) NOT (“Animals”[Mesh] NOT (“Animals”[Mesh] AND “Humans”[Mesh])) NOT (editorial[ptyp] OR comment[ptyp] OR news[ptyp] OR letter[ptyp] OR review[ptyp] OR systematic review[ptyp] OR systematic review[ti] OR meta-analysis[ptyp] OR meta-analysis[ti] OR meta-analyses[ti] OR retracted publication[ptyp] OR retraction of publication[ptyp] OR retraction of publication[tiab] OR retraction notice[ti]) Filters: Publication date from 2000/01/01 to 2019/10/08; English

#### Cochrane Central Register of Controlled Trials (CENTRAL)

- Provider: John Wiley & Sons
- Date(s) Searched: October 8, 2019
- Date range searched: January 1, 2000-October 8, 2019
- Search Terms:
  - #1 - (“dietary pattern*” OR “diet pattern*” OR “eating pattern*” OR “food pattern*” OR “diet quality*” OR “eating habit*” OR “dietary habit*” OR “diet habit*” OR “food habit*” OR “beverage habit*” OR [mh ^“Feeding Behavior”] OR “dietary profile*” OR “food profile*” OR “diet profile*” OR “eating profile*” OR “dietary guideline*” OR “dietary recommendation*” OR “dietary intake*” OR “eating style*” OR [mh “Diet, Mediterranean”] OR “Mediterranean Diet*” OR [mh “Dietary Approaches To Stop Hypertension”] OR “Dietary Approaches To Stop Hypertension Diet*” OR “DASH diet*” OR [mh “Diet, Gluten-Free”] OR “Gluten Free diet*” OR “prudent diet*” OR [mh “Diet, Paleolithic”] OR “Paleolithic Diet*” OR [mh “Diet, Vegetarian”] OR “vegetarian diet*” OR “vegan diet*” OR [mh “Diet, Healthy”] OR “plant based diet*” OR [mh “Diet, Western”] OR “western diet*” OR [mh “Diet, Carbohydrate-Restricted”] OR “low-carbohydrate diet*” OR “high carbohydrate diet*” OR “Ketogenic Diet*” OR “Nordic Diet*” OR [mh “Diet, Fat-Restricted”] OR [mh “Diet, High-Fat”] OR [mh “Diet, High-Protein”] OR “high protein diet*” OR “protein intake*” OR “high-fat diet*” OR “low fat diet*” OR [mh “Diet, Protein-Restricted”] OR “low protein diet*” OR [mh “Diet, Sodium-Restricted”] OR “low-sodium diet*” OR “low salt diet*”):ti,ab,kw
  - #2 - (([mh “Dietary Proteins”] OR “dietary protein*” OR [mh “Dietary Carbohydrates”] OR “dietary carbohydrate*” OR [mh “Dietary Fats”] OR “dietary fat*” OR hypocaloric OR hypo-caloric) NEAR/6 (diet OR diets OR consumption OR intake OR supplement*))
  - #3 - ([mh “Guideline Adherence”] OR guideline adherence*) NEAR/6 (diet OR dietary OR food OR beverage* OR nutrition*))
  - #4 - (“diet score*” OR “diet quality score*” OR “diet quality index*” OR kidmed OR “diet index*” OR “dietary index*” OR “food score*” OR MedDietScore OR “healthy eating index*”):ti,ab,kw
  - #5 - (((pattern OR patterns OR consumption OR habit*) NEAR/6 ([mh ^Diet] OR diet OR diets OR dietary OR [mh Food] OR food OR foods OR [mh Beverages] OR beverage OR beverages))):ti,ab,kw
  - #6 - #1 OR #2 OR #3 OR #4 OR #5
  - #7 - [mh Sarcopenia] OR [mh “Muscular Atrophy”] OR [mh “Muscle Fatigue”] OR [mh “Muscle Strength”] OR [mh “Physical Functional Performance”] OR [mh “Psychomotor Performance”]
  - #8 - (sarcopen* OR presarcopen* OR “muscular atroph*” OR “muscle fatigue” OR “muscle wast*” OR “muscle weak*” OR “muscle loss*” OR “muscle function*” OR “hand strength*” OR “grip strength*” OR handgrip OR “pinch strength*” OR “physical performance*” OR “psychomotor performance”):ti,ab,kw
  - #9 - ((muscle OR muscles OR [mh Muscles] OR [mh “Muscles, Skeletal”]) NEAR/3 ([mh Fatigue] OR fatigue OR weakness OR [mh Frailty] OR frail OR frailty OR [mh “Geriatric Assessment”] OR geriatric* OR [mh Osteoporosis] OR osteoporos* OR [mh “Age Factors”] OR [mh Aging] OR [mh Obesity] OR obesity OR [mh “Body Mass Index”] OR “body mass index” OR BMI OR “lean mass” OR “fat mass” OR [mh “Activities of Daily Living”] OR [mh “Quality of Life”] OR “quality of life” OR [mh “Postural Balance”] OR posture* OR [mh “Physical Exertion”] OR “physical exertion*” OR [mh “Motor Activity”] OR “motor activit*” OR [mh “Walking”] OR walking OR [mh Gait] OR gait)):ti,ab,kw
  - #10 - (([mh Aging] OR “older adult*”) NEAR/6 (“physical activit*” OR “physical function” OR “physical impairment” OR “functional limit*” OR “functional decline” OR [mh “Mobility Limitation”] OR “mobility limitation*” OR [mh Walking] OR walking OR [mh “Activities of Daily Living”] OR “activities of daily living” OR [mh “Independent Living”] OR “independent living” OR [mh “Quality of Life”] OR “quality of life”))
  - #11 - #7 OR #8 OR #9 OR #10
  - #12 - #6 AND #11” with Publication Year from 2000 to 2019 in Trials (Word variations have been searched)

#### Embase

- Provider: Elsevier
- Date(s) Searched: October 8, 2019
- Date range searched: January 1, 2000-October 8, 2019
- Search Terms:
  - #1 - ‘feeding behavior’/de OR ‘mediterranean diet’/exp OR ‘dash diet’/exp OR ‘gluten free diet’/exp OR ‘paleolithic diet’/de OR ‘vegetarian diet’/exp OR ‘healthy diet’/de OR ‘western diet’/de OR ‘low carbohydrate diet’/exp OR ‘low fat diet’/de OR ‘lipid diet’/exp OR ‘protein diet’/exp OR ‘protein restriction’/de OR ‘sodium restriction’/de
  - #2 - ‘dietary pattern*’:ab,ti OR ‘diet pattern*’:ab,ti OR ‘eating pattern*’:ab,ti OR ‘food pattern*’:ab,ti OR ‘diet quality*’:ab,ti OR ‘eating habit*’:ab,ti OR ‘dietary habit*’:ab,ti OR ‘diet habit*’:ab,ti OR ‘food habit*’:ab,ti OR ‘beverage habit*’:ab,ti OR ‘dietary profile*’:ab,ti OR ‘food profile*’:ab,ti OR ‘diet profile*’:ab,ti OR ‘eating profile*’:ab,ti OR ‘dietary guideline*’:ab,ti OR ‘dietary recommendation*’:ab,ti OR ‘dietary intake*’:ab,ti OR ‘eating style*’:ab,ti OR ‘mediterranean diet*’:ab,ti OR ‘dietary approaches to stop hypertension diet*’:ab,ti OR ‘dash diet*’:ab,ti OR ‘gluten free diet*’:ab,ti OR ‘prudent diet*’:ab,ti OR ‘paleolithic diet*’:ab,ti OR ‘vegetarian diet*’:ab,ti OR ‘vegan diet*’:ab,ti OR ‘plant based diet*’:ab,ti OR ‘western diet*’:ab,ti OR ‘low-carbohydrate diet*’:ab,ti OR ‘high carbohydrate diet*’:ab,ti OR ‘ketogenic diet*’:ab,ti OR ‘nordic diet*’:ab,ti OR ‘high protein diet*’:ab,ti OR ‘protein intake*’:ab,ti OR ‘high-fat diet*’:ab,ti OR ‘low fat diet*’:ab,ti OR ‘low protein diet*’:ab,ti OR ‘low-sodium diet*’:ab,ti OR ‘low salt diet*’:ab,ti
  - #3 - ((‘dietary protein*’ OR ‘dietary carbohydrate*’ OR ‘dietary fat*’ OR hypocaloric OR hypo-caloric) NEAR/6 (diet OR diets OR consumption OR intake OR supplement)):ab,ti
  - #4 - (‘guideline adherence’ NEAR/6 (diet OR dietary OR food OR beverage OR nutrition*)):ab,ti
  - #5 - ‘diet score’:ab,ti OR ‘diet quality score’:ab,ti OR kidmed:ab,ti OR ‘diet index’:ab,ti OR ‘dietary index’:ab,ti OR ‘diet quality index’:ab,ti OR ‘food score’:ab,ti OR meddietscore:ab,ti OR ‘healthy eating index’:ab,ti
  - #6 - ((pattern OR patterns OR consumption OR habit*) NEAR/6 (diet OR diets OR dietary OR food OR foods OR beverage OR beverages)):ab,ti
  - #7 - #1 OR #2 OR #3 OR #4 OR #5 OR #6
  - #8 - ‘sarcopenia’/de OR ‘muscle atrophy’/de OR ‘muscle fatigue’/de OR ‘muscle strength’/de OR ‘physical performance’/exp OR ‘psychomotor performance’/exp
  - #9 - sarcopen*:ab,ti OR presarcopen*:ab,ti OR ‘muscular atroph*’:ab,ti OR ‘muscle fatigue*’:ab,ti OR ‘muscle wast*’:ab,ti OR ‘muscle weak*’:ab,ti OR ‘muscle loss*’:ab,ti OR ‘muscle function*’:ab,ti OR ‘hand strength*’:ab,ti OR ‘grip strength*’:ab,ti OR handgrip*:ab,ti OR ‘pinch strength*’:ab,ti OR ‘physical performance*’:ab,ti OR ‘psychomotor performance’:ab,ti
  - #10 - ((muscle OR muscles) NEAR/3 (fatigue OR weakness OR frail OR frailty OR geriatric* OR osteoporos* OR ‘age factor*’ OR aging OR obesity OR ‘body mass index’ OR bmi OR ‘lean mass’ OR ‘fat mass’ OR ‘daily life activity’ OR ‘quality of life’ OR ‘body equilibrium’ OR posture* OR ‘physical exertion*’ OR ‘motor activit*’ OR walking OR gait)):ab,ti
  - #11 - ((aging OR ‘older adult*’) NEAR/6 (‘physical activit*’ OR ‘physical function’ OR ‘physical impairment’ OR ‘functional limit*’ OR ‘functional decline’ OR ‘mobility limitation*’ OR walking OR ‘activities of daily living’ OR ‘independent living’ OR ‘quality of life’)):ab,ti
  - #12 - #8 OR #9 OR #10 OR #11
  - #13 - #7 AND #12
  - #14 - #7 AND #12 AND ([article]/lim OR [article in press]/lim) AND [humans]/lim AND [english]/lim AND [2000-2019]/py NOT ([conference abstract]/lim OR [conference review]/lim OR [conference paper]/lim OR [editorial]/lim OR [erratum]/lim OR [letter]/lim OR [note]/lim OR [review]/lim OR [systematic review]/lim OR [meta analysis]/lim)

## LITERATURE SEARCH AND SCREENING RESULTS

The flow chart (Figure 2) below illustrates the literature search and screening results for articles examining the systematic review question. The results of the electronic database searches, after removal of duplicates, were screened independently by two NESR analysts using a step-wise process by reviewing titles, abstracts, and full-texts to determine which articles met the inclusion criteria. Refer to Table 5 for the rationale for exclusion for each excluded full-text article. A manual search was done to find articles that were not identified when searching the electronic databases; all manually identified articles are also screened to determine whether they meet criteria for inclusion.

Figure 2 Flow chart of literature search and screening results

This flow chart illustrates the literature search and screening results for articles examining the relationship between dietary patterns and sarcopenia. The literature search yielded 7314 articles. During title screening, 3842 articles were screened out. During abstract screening, 2848 were screened out. During full-text screening, 620 articles were screened out. During the hand search, 0 additional articles were identified to include. A total of 4 articles were included in the systematic review at the end of the search and screening process.

### Excluded Articles

The table below lists the articles excluded after full-text screening, and includes columns for the categories of inclusion and exclusion criteria (see Table 1) that studies were excluded based on. At least one reason for exclusion is provided for each article, as indicated by an “X” in one of the columns, though this may not reflect all possible reasons for exclusion. Information about articles excluded after title and abstract screening is available upon request.

Table 5 Articles excluded after full text screening with rationale for exclusion

| Citation | Study Design | Intervention/Exposure | Comparator | Outcome | Publication Status | Language | Country | Health Status
1. | Preserve muscle mass--and prevent falls--with proper nutrition. Protein, vitamin D, and a balanced diet counter the effects of low muscle mass, promoting strength and mobility as we age. Duke Med Health News. 2013. 19:3–4 https://www.ncbi.nlm.nih.gov/pubmed/23802327 | X | | | | X
2. | Antoneta Granic, Carol Jagger, Karen Davies, Ashley Adamson, Thomas Kirkwood, Tom R Hill, Mario Siervo, John C Mathers, Avan Aihie Sayer Effect of Dietary Patterns on Muscle Strength and Physical Performance in the Very Old: Findings from the Newcastle 85+ Study. PloS one. 2016. 11:e0149699 https://www.ncbi.nlm.nih.gov/pubmed/26934360 26934360 | | | | X
3. | Abbatecola, A. M.,Cherubini, A.,Guralnik, J. M.,Andres Lacueva, C.,Ruggiero, C., Maggio, M.,Bandinelli, S.,Paolisso, G.,Ferrucci, L. Plasma polyunsaturated fatty acids and age-related physical performance decline. Rejuvenation Res. 2009. 12:25–32 https://www.ncbi.nlm.nih.gov/pubmed/19196012 https://www.ncbi.nlm.nih.gov/pmc/articles/PMC2674224/pdf/rej.2008.0799.pdf 19196012 | X | X
4. | Achten, J.,Halson, S. L.,Moseley, L.,Rayson, M. P.,Casey, A.,Jeukendrup, A. E. Higher dietary carbohydrate content during intensified running training results in better maintenance of performance and mood state. J Appl Physiol (1985). 2004. 96:1331–40 https://www.ncbi.nlm.nih.gov/pubmed/14660506 https://www.physiology.org/doi/pdf/10.1152/japplphysiol.00973.2003 14660506 | | | | X | | | | X
5. | Actrn, Does nutrition and exercise prevent frailty and reduce falls in pre-frail older adults in New Zealand?. Http://www.who.int/trialsearch/trial2.aspx? Trialid=actrn12614000827639. 2014. #volume#:#pages# https://www.cochranelibrary.com/central/doi/10.1002/central/CN-01800174/full | X | | | | X
6. | Agarwal, P.,Wang, Y.,Buchman, A. S.,Bennett, D. A.,Morris, M. C. Dietary Patterns and Self-reported Incident Disability in Elderly. J Gerontol A Biol Sci Med Sci. 2018. #volume#:#pages# https://www.ncbi.nlm.nih.gov/pubmed/30247552 | | | | X
7. | Aguirre, N.,van Loon, L. J.,Baar, K. The role of amiX acids in skeletal muscle adaptation to exercise. Nestle Nutr Inst Workshop Ser. 2013. 76:85–102 https://www.ncbi.nlm.nih.gov/pubmed/23899757 https://www.karger.com/Article/Abstract/350261 23899757 | X | X
8. | Ahola, S.,Auranen, M.,Isohanni, P.,Niemisalo, S.,Urho, N.,Buzkova, J.,Velagapudi, V.,Lundbom, N.,Hakkarainen, A.,Muurinen, T.,Piirilä, P.,Pietiläinen, K. H., Suomalainen, A. Modified Atkins diet induces subacute selective ragged-red-fiber lysis in mitochondrial myopathy patients. EMBO Molecular Medicine. 2016. 8:1234–1247 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L612294551 10.15252/emmm.201606592 27647878 | | | | X | | | | X
9. | Ainslie, P. N.,Campbell, I. T.,Frayn, K. N.,Humphreys, S. M.,MacLaren, D. P.,Reilly, T.,Westerterp, K. R. Energy balance, metabolism, hydration, and performance during strenuous hill walking: the effect of age. J Appl Physiol (1985). 2002. 93:714–23 https://www.ncbi.nlm.nih.gov/pubmed/12133883 https://www.physiology.org/doi/pdf/10.1152/japplphysiol.01249.2001 12133883 | | X | X
10. | Alemán-Mateo, H.,Carreón, V. R.,Macías, L.,Astiazaran-García, H.,Gallegos-Aguilar, A. C.,Enríquez, J. R. Nutrient-rich dairy proteins improve appendicular skeletal muscle mass and physical performance, and attenuate the loss of muscle strength in older men and women subjects: a single-blind randomized clinical trial. Clinical interventions in aging. 2014. 9:1517–1525 https://www.cochranelibrary.com/central/doi/10.1002/central/CN-01013922/full 25258523 | | X
11. | Alexandrov, N. V.,Eelderink, C.,Singh-Povel, C. M.,Navis, G. J.,Bakker, S. J. L., Corpeleijn, E. Dietary Protein Sources and Muscle Mass over the Life Course: The Lifelines Cohort Study. Nutrients. 2018. 10:#pages# https://www.ncbi.nlm.nih.gov/pubmed/30308987 https://res.mdpi.com/nutrients/nutrients-10-01471/article_deploy/nutrients-10-01471.pdf?filename=&attachment=1 | X
12. | Allaert, F. A.,Guerin-Deremaux, L.,Mauray-Soulier, A.,Saniez-Degrave, M. H. Evaluation of adherence by elderly nursing home patients to regular consumption of apple compote enriched with protein and soluble fiber. Aging Clin Exp Res. 2016. 28:189–95 https://www.ncbi.nlm.nih.gov/pubmed/26240032 https://www.ncbi.nlm.nih.gov/pmc/articles/PMC4794522/pdf/40520_2015_Article_415.pdf 26240032 | | X | | X
13. | Alves, C. R.,Merege Filho, C. A.,Benatti, F. B.,Brucki, S.,Pereira, R. M.,de Sa Pinto, A. L.,Lima, F. R.,Roschel, H.,GualaX, B. Creatine supplementation associated or not with strength training upon emotional and cognitive measures in older women: a randomized double-blind study. PLoS One. 2013. 8:e76301 https://www.ncbi.nlm.nih.gov/pubmed/24098469 https://www.ncbi.nlm.nih.gov/pmc/articles/PMC3789718/pdf/pone.0076301.pdf 24098469 | | X
14. | Alves, C. R.,Pasqua, L.,Artioli, G. G.,Roschel, H.,Solis, M.,Tobias, G.,Klansener, C.,Bertuzzi, R.,Franchini, E.,Lancha Junior, A. H.,Gualano, B. Anthropometric, physiological, performance, and nutritional profile of the Brazil National Canoe Polo Team. J Sports Sci. 2012. 30:305–11 https://www.ncbi.nlm.nih.gov/pubmed/22168392 https://www.tandfonline.com/doi/full/10.1080/02640414.2011.638086 22168392 | X | X
15. | Anderson, A. L.,Harris, T. B.,Tylavsky, F. A.,Perry, S. E.,Houston, D. K.,Hue, T. F., Strotmeyer, E. S.,Sahyoun, N. R. Dietary patterns and survival of older adults. J Am Diet Assoc. 2011. 111:84–91 https://www.ncbi.nlm.nih.gov/pubmed/21185969 21185969 | | | | X
16. | Andrews, R. D.,MacLean, D. A.,Riechman, S. E. Protein intake for skeletal muscle hypertrophy with resistance training in seniors. Int J Sport Nutr Exerc Metab. 2006. 16:362–72 https://www.ncbi.nlm.nih.gov/pubmed/17136939 17136939 | X | X | X
17. | Andrich, D. E.,Filion, M. E.,Woods, M.,Dwyer, J. T.,Gorbach, S. L.,Goldin, B. R., Adlercreutz, H.,Aubertin-Leheudre, M. Relationship between essential amino acids and muscle mass, independent of habitual diets, in pre- and post-menopausal US women. Int J Food Sci Nutr. 2011. 62:719–24 https://www.ncbi.nlm.nih.gov/pubmed/21568818 https://www.tandfonline.com/doi/pdf/10.3109/09637486.2011.573772?needAccess=true 21568818 | X | X
18. | Aparicio, V. A.,Coll-Risco, I.,Borges-Cosic, M.,Acosta-Manzano, P. Exercise and the mediterranean diet for the prevention and treatment of cardiometabolic abnormalities induced by menopause. The flamenco study. Journal of physiology and biochemistry. 2018. 74:S12–S13 https://www.cochranelibrary.com/central/doi/10.1002/central/CN-01770599/full | X
19. | Aparicio, V. A.,Ruiz-Cabello, P.,Borges-Cosic, M.,Andrade, A.,Coll-Risco, I.,Acosta-Manzano, P.,Soriano-Maldonado, A. Association of physical fitness, body composition, cardiometabolic markers and adherence to the Mediterranean diet with bone mineral density in perimenopausal women. The FLAMENCO project. J Sports Sci. 2017. 35:880–887 https://www.ncbi.nlm.nih.gov/pubmed/27310097 https://www.tandfonline.com/doi/full/10.1080/02640414.2016.1196825 27310097 | X | X | | X
20. | Aptekmann, N. P.,Cesar, T. B. Orange juice improved lipid profile and blood lactate of overweight middle-aged women subjected to aerobic training. Maturitas. 2010. 67:343–7 https://www.ncbi.nlm.nih.gov/pubmed/20729016 https://www.sciencedirect.com/science/article/pii/S0378512210003075?via%3Dihub 20729016 | | X
21. | Arentson-Lantz, E. J.,Galvan, E.,Ellison, J.,Wacher, A.,Paddon-Jones, D. Improving Dietary Protein Quality Reduces the Negative Effects of Physical Inactivity on Body Composition and Muscle Function. J Gerontol A Biol Sci Med Sci. 2019. 74:1605–1611 https://www.ncbi.nlm.nih.gov/pubmed/30689727 30689727 | | X | | X
22. | Argyridou, S.,Zaccardi, F.,Davies, M. J.,Khunti, K.,Yates, T. Relevance of physical function in the association of red and processed meat intake with all-cause, cardiovascular, and cancer mortality. Nutr Metab Cardiovasc Dis. 2019. #volume#:#pages# https://www.ncbi.nlm.nih.gov/pubmed/31377183 | | X | | X
23. | Arias-Fernandez, L.,Machado-Fragua, M. D.,Graciani, A.,Guallar-Castillon, P., Banegas, J. R.,Rodriguez-Artalejo, F.,Lana, A.,Lopez-Garcia, E. Prospective Association Between Nut Consumption and Physical Function in Older Men and Women. J Gerontol A Biol Sci Med Sci. 2018. #volume#:#pages# https://www.ncbi.nlm.nih.gov/pubmed/30052782 https://academic.oup.com/biomedgerontology/advance-article-abstract/doi/10.1093/gerona/gly171/5056957?redirectedFrom=fulltext | | X
24. | Armamento-Villareal, R.,Aguirre, L.,Napoli, N.,Shah, K.,Hilton, T.,Sinacore, D. R., Qualls, C.,Villareal, D. T. Changes in thigh muscle volume predict bone mineral density response to lifestyle therapy in frail, obese older adults. Osteoporos Int. 2014. 25:551–8 https://www.ncbi.nlm.nih.gov/pubmed/23892583 https://www.ncbi.nlm.nih.gov/pmc/articles/PMC3903658/pdf/nihms528844.pdf 23892583 | | X
25. | Arnarson, A.,Gudny Geirsdottir, O.,Ramel, A.,Briem, K.,Jonsson, P. V.,Thorsdottir, I. Effects of whey proteins and carbohydrates on the efficacy of resistance training in elderly people: Double blind, randomised controlled trial. European Journal of Clinical Nutrition. 2013. 67:821–826 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L52488267 10.1038/ejcn.2013.40 23486511 | | X
26. | Asamane, E. A.,Greig, C. A.,Aunger, J. A.,Thompson, J. L. Perceptions and factors influencing eating behaviours and physical function in community-dwelling ethnically diverse older adults: A longitudinal qualitative study. Nutrients. 2019. 11:#pages# http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L2002186069 10.3390/nu11061224 | | X | | X
27. | Assmann, K. E.,Andreeva, V. A.,Camilleri, G. M.,Verger, E. O.,Jeandel, C., Hercberg, S.,Galan, P.,Kesse-Guyot, E. Dietary scores at midlife and healthy ageing in a French prospective cohort. Br J Nutr. 2016. 116:666–76 https://www.ncbi.nlm.nih.gov/pubmed/27301412 27301412 | | | | X
28. | Assmann, K. E.,Lassale, C.,Andreeva, V. A.,Jeandel, C.,Hercberg, S.,Galan, P., Kesse-Guyot, E. A Healthy Dietary Pattern at Midlife, Combined with a Regulated Energy Intake, Is Related to Increased Odds for Healthy Aging. J Nutr. 2015. 145:2139–45 https://www.ncbi.nlm.nih.gov/pubmed/26246320 26246320 | | | | X
29. | Aubertin-Leheudre, M.,Adlercreutz, H. Relationship between animal protein intake and muscle mass index in healthy women. Br J Nutr. 2009. 102:1803–10 https://www.ncbi.nlm.nih.gov/pubmed/19678968 https://www.cambridge.org/core/services/aop-cambridge-core/content/view/FDD4EBFB12C8089E4FF69555FF6BB98C/S0007114509991310a.pdf/div-class-title-relationship-between-animal-protein-intake-and-muscle-mass-index-in-healthy-women-div.pdf 19678968 | X
30. | Aubertin-Leheudre, M.,Lord, C.,Labonte, M.,Khalil, A.,Dionne, I. J. Relationship between sarcopenia and fracture risks in obese postmenopausal women. J Women Aging. 2008. 20:297–308 https://www.ncbi.nlm.nih.gov/pubmed/18983113 18983113 | X | X | | X
31. | Aubry, E.,Aeberhard, C.,Bally, L.,Nuoffer, J. M.,Risch, L.,Muhlebach, S.,Burgunder, J. M.,Stanga, Z. Are patients affected by mitochondrial disorders at nutritional risk?. Nutrition. 2018. 47:56–62 https://www.ncbi.nlm.nih.gov/pubmed/29429536 https://www.sciencedirect.com/science/article/pii/S0899900717302125?via%3Dihub 29429536 | | X | | | | | | X
32. | Backx, E. M.,Tieland, M.,Borgonjen-van den Berg, K. J.,Claessen, P. R.,van Loon, L. J.,de Groot, L. C. Protein intake and lean body mass preservation during energy intake restriction in overweight older adults. Int J Obes (Lond). 2016. 40:299–304 https://www.ncbi.nlm.nih.gov/pubmed/26471344 https://www.nature.com/articles/ijo2015182.pdf 26471344 | | | | X
33. | Baguet, A.,Everaert, I.,De Naeyer, H.,Reyngoudt, H.,Stegen, S.,Beeckman, S., Achten, E.,Vanhee, L.,Volkaert, A.,Petrovic, M.,Taes, Y.,Derave, W. Effects of sprint training combined with vegetarian or mixed diet on muscle carnosine content and buffering capacity. Eur J Appl Physiol. 2011. 111:2571–80 https://www.ncbi.nlm.nih.gov/pubmed/21373871 https://link.springer.com/content/pdf/10.1007%2Fs00421-011-1877-4.pdf 21373871 | | | | X
34. | Baier, S.,Johannsen, D.,Abumrad, N.,Rathmacher, J. A.,Nissen, S.,Flakoll, P. Year-long changes in protein metabolism in elderly men and women supplemented with a nutrition cocktail of beta-hydroxy-beta-methylbutyrate (HMB), L-arginine, and L-lysine. JPEN J Parenter Enteral Nutr. 2009. 33:71–82 https://www.ncbi.nlm.nih.gov/pubmed/19164608 https://onlinelibrary.wiley.com/doi/pdf/10.1177/0148607108322403 19164608 | | X
35. | Baker, M. E.,DeCesare, K. N.,Johnson, A.,Kress, K. S.,Inman, C. L.,Weiss, E. P. Short-Term Mediterranean Diet Improves Endurance Exercise Performance: A Randomized-Sequence Crossover Trial. J Am Coll Nutr. 2019. #volume#:1–9 https://www.ncbi.nlm.nih.gov/pubmed/30758261 | | | | X | | | | X
36. | Bakker, L. E.,van Schinkel, L. D.,Guigas, B.,Streefland, T. C.,Jonker, J. T.,van Klinken, J. B.,van der Zon, G. C.,Lamb, H. J.,Smit, J. W.,Pijl, H.,Meinders, A. E., Jazet, I. M. A 5-day high-fat, high-calorie diet impairs insulin sensitivity in healthy, young South Asian men but not in Caucasian men. Diabetes. 2014. 63:248–58 https://www.ncbi.nlm.nih.gov/pubmed/24357702 http://hw-f5-diabetes.highwire.org/content/diabetes/63/1/248.full.pdf 24357702 | X | | | X
37. | Barbat-Artigas, S.,Dupontgand, S.,Fex, A.,Karelis, A. D.,Aubertin-Leheudre, M. Relationship between dynapenia and cardiorespiratory functions in healthy postmenopausal women: novel clinical criteria. Menopause. 2011. 18:400–5 https://www.ncbi.nlm.nih.gov/pubmed/21107297 21107297 | X | X
38. | Barnekow-Bergkvist, M.,Hedberg, G.,Janlert, U.,Jansson, E. Adolescent determinants of cardiovascular risk factors in adult men and women. Scand J Public Health. 2001. 29:208–17 https://www.ncbi.nlm.nih.gov/pubmed/11680773 11680773 | | X
39. | Barrea, L.,Muscogiuri, G.,Di Somma, C.,Tramontano, G.,De Luca, V.,Illario, M., Colao, A.,Savastano, S. Association between Mediterranean diet and hand grip strength in older adult women. Clin Nutr. 2019. 38:721–729 https://www.ncbi.nlm.nih.gov/pubmed/29643004 https://www.sciencedirect.com/science/article/pii/S0261561418301249?via%3Dihub 29643004 | X
40. | Bartali, B.,Frongillo, E. A.,Stipanuk, M. H.,Bandinelli, S.,Salvini, S.,Palli, D.,Morais, J. A.,Volpato, S.,Guralnik, J. M.,Ferrucci, L. Protein intake and muscle strength in older persons: does inflammation matter?. J Am Geriatr Soc. 2012. 60:480–4 https://www.ncbi.nlm.nih.gov/pubmed/22283208 https://www.ncbi.nlm.nih.gov/pmc/articles/PMC3390191/pdf/nihms339875.pdf 22283208 | | X
41. | Baruth, M.,Wilcox, S.,McClenaghan, B.,Becofsky, K.,Schoffman, D. E. Clinically meaningful changes in functional performance resulting from self-directed interventions in individuals with arthritis. Public health. 2016. 133:116–123 https://www.cochranelibrary.com/central/doi/10.1002/central/CN-01154725/full 26874892 | | X | | | | | | X
42. | Bauer, J. M.,Verlaan, S.,Bautmans, I.,Brandt, K.,Donini, L. M.,Maggio, M.,McMurdo, M. E.,Mets, T.,Seal, C.,Wijers, S. L.,Ceda, G. P.,De Vito, G.,Donders, G.,Drey, M.,Greig, C.,Holmback, U.,Narici, M.,McPhee, J.,Poggiogalle, E.,Power, D.,Scafoglieri, A.,Schultz, R.,Sieber, C. C.,Cederholm, T. Effects of a vitamin D and leucine-enriched whey protein nutritional supplement on measures of sarcopenia in older adults, the PROVIDE study: a randomized, double-blind, placebo-controlled trial. J Am Med Dir Assoc. 2015. 16:740–7 https://www.ncbi.nlm.nih.gov/pubmed/26170041 26170041 | | X
43. | Baumgartner, R. N. Body composition in healthy aging. Ann N Y Acad Sci. 2000. 904:437–48 https://www.ncbi.nlm.nih.gov/pubmed/10865787 https://nyaspubs.onlinelibrary.wiley.com/doi/pdf/10.1111/j.1749-6632.2000.tb06498.x 10865787 | X | X
44. | Bayán-Bravo, A.,Pérez-Tasigchana, R. F.,Sayón-Orea, C.,Martínez-Gómez, D., López-García, E.,Rodríguez-Artalejo, F.,Guallar-Castillón, P. Combined impact of traditional and non-traditional healthy behaviors on health-related quality of Life: A prospective study in older adults. PLoS ONE. 2017. 12:#pages# http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L614210164 10.1371/journal.pone.0170513 | | | | X
45. | Beasley, J. M.,Lacroix, A. Z.,Neuhouser, M. L.,Huang, Y.,Tinker, L.,Woods, N., Michael, Y.,Curb, J. D.,Prentice, R. L. Protein intake and incident frailty in the women’s health initiative observational study. Journal of the American Geriatrics Society. 2010. 58:1063–1071 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L358945013 10.1111/j.1532-5415.2010.02866.x 20487071 | | X
46. | Beasley, J. M.,Sevick, M. A.,Kirshner, L.,Mangold, M.,Chodosh, J. Congregate Meals: Opportunities to Help Vulnerable Older Adults Achieve Diet and Physical Activity Recommendations. J Frailty Aging. 2018. 7:182–186 https://www.ncbi.nlm.nih.gov/pubmed/30095149 30095149 | X
47. | Beasley, J. M.,Wertheim, B. C.,LaCroix, A. Z.,Prentice, R. L.,Neuhouser, M. L., Tinker, L. F.,Kritchevsky, S.,Shikany, J. M.,Eaton, C.,Chen, Z.,Thomson, C. A. Biomarker-calibrated protein intake and physical function in the Women’s Health Initiative. J Am Geriatr Soc. 2013. 61:1863–71 https://www.ncbi.nlm.nih.gov/pubmed/24219187 https://www.ncbi.nlm.nih.gov/pmc/articles/PMC3928025/pdf/nihms554126.pdf 24219187 | | X
48. | Bechshoft, R. L.,Reitelseder, S.,Hojfeldt, G.,Castro-Mejia, J. L.,Khakimov, B.,Ahmad, H. F.,Kjaer, M.,Engelsen, S. B.,Johansen, S. M.,Rasmussen, M. A.,Lassen, A. J.,Jensen, T.,Beyer, N.,Serena, A.,Perez-Cueto, F. J.,Nielsen, D. S., Jespersen, A. P.,Holm, L. Counteracting Age-related Loss of Skeletal Muscle Mass: a clinical and ethnological trial on the role of protein supplementation and training load (CALM Intervention Study): study protocol for a randomized controlled trial. Trials. 2016. 17:397 https://www.ncbi.nlm.nih.gov/pubmed/27507236 https://www.ncbi.nlm.nih.gov/pmc/articles/PMC4977774/pdf/13063_2016_Article_1512.pdf 27507236 | X
49. | Beck, A. M.,Damkjaer, K.,Beyer, N. Multifaceted nutritional intervention among nursing-home residents has a positive influence on nutrition and function. Nutrition. 2008. 24:1073–80 https://www.ncbi.nlm.nih.gov/pubmed/18586458 https://www.sciencedirect.com/science/article/pii/S0899900708002189?via%3Dihub 18586458 | | X
50. | Beck, A. M.,Rask, KØ,Leedo, E.,Jensen, L. L.,Martins, K.,Vedelspang, A. Nutritional support in a cross-sector model for the rehabilitation of geriatric patients: a randomised controlled trial. Clinical nutrition (edinburgh, scotland). 2014. 33:S37- https://www.cochranelibrary.com/central/doi/10.1002/central/CN-01053089/full | | | | | X
51. | Beelen, J.,de Roos, N. M.,de Groot, Lcpgm A 12-week intervention with protein-enriched foods and drinks improved protein intake but not physical performance of older patients during the first 6 months after hospital release: a randomised controlled trial. Br J Nutr. 2017. 117:1541–1549 https://www.ncbi.nlm.nih.gov/pubmed/28662731 https://www.cambridge.org/core/services/aop-cambridge-core/content/view/183D909E5E48458A1C4FF0411B364101/S0007114517001477a.pdf/div-class-title-a-12-week-intervention-with-protein-enriched-foods-and-drinks-improved-protein-intake-but-not-physical-performance-of-older-patients-during-the-first-6-months-after-hospital-release-a-randomised-controlled-trial-div.pdf 28662731 | | X | | | | | | X
52. | Bell, K. E.,Snijders, T.,Zulyniak, M.,Kumbhare, D.,Parise, G.,Chabowski, A.,Phillips, S. M. A whey protein-based multi-ingredient nutritional supplement stimulates gains in lean body mass and strength in healthy older men: A randomized controlled trial. PLoS One. 2017. 12:e0181387 https://www.ncbi.nlm.nih.gov/pubmed/28719669 https://www.ncbi.nlm.nih.gov/pmc/articles/PMC5515445/pdf/pone.0181387.pdf 28719669 | | X
53. | Beller, G.,Belavy, D. L.,Sun, L.,Armbrecht, G.,Alexandre, C.,Felsenberg, D. WISE-2005: bed-rest induced changes in bone mineral density in women during 60 days simulated microgravity. Bone. 2011. 49:858–66 https://www.ncbi.nlm.nih.gov/pubmed/21723970 https://www.sciencedirect.com/science/article/pii/S8756328211010623?via%3Dihub 21723970 | | X | | X | | | | X
54. | Berg, A.,Frey, I.,Deibert, P.,Landmann, U.,Konig, D.,Schmidt-Trucksass, A.,Rucker, G.,Kreiter, H.,Berg, A.,Dickhuth, H. H. Weight reduction is feasible - Preliminary results of a controlled, randomised intervention study in overweight adults. Ernahrungs umschau. 2003. 50:386–393+374 https://www.cochranelibrary.com/central/doi/10.1002/central/CN-01754472/full | | | | | X | X
55. | Bernstein, M. A.,Tucker, K. L.,Ryan, N. D.,O’Neill, E. F.,Clements, K. M.,Nelson, M. E.,Evans, W. J.,Fiatarone Singh, M. A. Higher dietary variety is associated with better nutritional status in frail elderly people. J Am Diet Assoc. 2002. 102:1096–104 https://www.ncbi.nlm.nih.gov/pubmed/12171454 12171454 | | | | X
56. | Berryman, C. E.,Sepowitz, J. J.,McClung, H. L.,Lieberman, H. R.,Farina, E. K., McClung, J. P.,Ferrando, A. A.,Pasiakos, S. M. Supplementing an energy adequate, higher protein diet with protein does not enhance fat-free mass restoration after short-term severe negative energy balance. J Appl Physiol (1985). 2017. 122:1485–1493 https://www.ncbi.nlm.nih.gov/pubmed/28385919 28385919 | | | | | | | | X
57. | Bertoli, S.,Magni, P.,Krogh, V.,Ruscica, M.,Dozio, E.,Testolin, G.,Battezzati, A. Is ghrelin a signal of decreased fat-free mass in elderly subjects?. Eur J Endocrinol. 2006. 155:321–30 https://www.ncbi.nlm.nih.gov/pubmed/16868147 16868147 | | X
58. | Bezrati-Benayed, I.,Nasrallah, F.,Feki, M.,Chamari, K.,Omar, S.,Alouane-Trabelsi, L.,Ben Mansour, A.,Kaabachi, N. Urinary creatine at rest and after repeated sprints in athletes: a pilot study. Biol Sport. 2014. 31:49–54 https://www.ncbi.nlm.nih.gov/pubmed/24917689 24917689 | | X | | X | | | | X
59. | Bhasin, S.,Apovian, C. M.,Travison, T. G.,Pencina, K.,Moore, L. L.,Huang, G., Campbell, W. W.,Li, Z.,Howland, A. S.,Chen, R.,Knapp, P. E.,Singer, M. R.,Shah, M.,Secinaro, K.,Eder, R. V.,Hally, K.,Schram, H.,Bearup, R.,Beleva, Y. M., McCarthy, A. C.,Woodbury, E.,McKinnon, J.,Fleck, G.,Storer, T. W.,Basaria, S. Effect of Protein Intake on Lean Body Mass in Functionally Limited Older Men: A Randomized Clinical Trial. JAMA Intern Med. 2018. 178:530–541 https://www.ncbi.nlm.nih.gov/pubmed/29532075 29532075 | | X
60. | Bibas, L.,Levi, M.,Bendayan, M.,Mullie, L.,Forman, D. E.,Afilalo, J. Therapeutic interventions for frail elderly patients: Part I: Published randomized trials. Progress in Cardiovascular Diseases. 2014. 57:134–143 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L604626599 10.1016/j.pcad.2014.07.004 25216612 | X
61. | Bilsborough, J. C.,Greenway, K.,Livingston, S.,Cordy, J.,Coutts, A. J. Changes in Anthropometry, Upper-Body Strength, and Nutrient Intake in Professional Australian Football Players During a Season. International journal of sports physiology and performance. 2016. 11:290–300 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L615156012 10.1123/ijspp.2014-0447 26217046 | | X | | X | | | | X
62. | Bingham, C. M.,Lahti-Koski, M.,Absetz, P.,Puukka, P.,Kinnunen, M.,Pihlajamaki, H.,Sahi, T.,Uutela, A.,Jallinoja, P. Food choices and health during military service: increases in sugar- and fibre-containing foods and changes in anthropometric and clinical risk factors. Public Health Nutr. 2012. 15:1248–55 https://www.ncbi.nlm.nih.gov/pubmed/22166515 22166515 | | | | | | | | X
63. | Binns, A.,Gray, M.,Henson, A. C.,Fort, I. L. Changes in Lean Mass and Serum Myostatin with Habitual Protein Intake and High-Velocity Resistance Training. J Nutr Health Aging. 2017. 21:1111–1117 https://www.ncbi.nlm.nih.gov/pubmed/29188869 29188869 | X | X | | X
64. | Birnie, K.,Ben-Shlomo, Y.,Gunnell, D.,Ebrahim, S.,Bayer, A.,Gallacher, J.,Holly, J. M.,Martin, R. M. Childhood milk consumption is associated with better physical performance in old age. Age Ageing. 2012. 41:776–84 https://www.ncbi.nlm.nih.gov/pubmed/22542496 22542496 | | X
65. | Bischoff-Ferrari, H. A.,Dietrich, T.,Orav, E. J.,Hu, F. B.,Zhang, Y.,Karlson, E. W., Dawson-Hughes, B. Higher 25-hydroxyvitamin D concentrations are associated with better lower-extremity function in both active and inactive persons aged > or =60 y. Am J Clin Nutr. 2004. 80:752–8 https://www.ncbi.nlm.nih.gov/pubmed/15321818 15321818 | X | X
66. | Bishop, N. J.,Zuniga, K. E.,Lucht, A. L. Latent Profiles of Macronutrient Density and their Association with Mobility Limitations in an Observational Longitudinal Study of Older U.S. Adults. J Nutr Health Aging. 2018. 22:645–654 https://www.ncbi.nlm.nih.gov/pubmed/29806853 29806853 | | | | X
67. | Blundell, J. E.,Caudwell, P.,Gibbons, C.,Hopkins, M.,Naslund, E.,King, N. A., Finlayson, G. Body composition and appetite: fat-free mass (but not fat mass or BMI) is positively associated with self-determined meal size and daily energy intake in humans. Br J Nutr. 2012. 107:445–9 https://www.ncbi.nlm.nih.gov/pubmed/21733267 21733267 | | X | | X
68. | Bohannon, R. W. Population representative gait speed and its determinants. J Geriatr Phys Ther. 2008. 31:49–52 https://www.ncbi.nlm.nih.gov/pubmed/19856549 19856549 | X | X
69. | Boidin, M.,Lapierre, G.,Paquette Tanir, L.,Nigam, A.,Juneau, M.,Guilbeault, V., Latour, E.,Gayda, M. Effect of aquatic interval training with Mediterranean diet counseling in obese patients: results of a preliminary study. Ann Phys Rehabil Med. 2015. 58:269–75 https://www.ncbi.nlm.nih.gov/pubmed/26233941 26233941 | | X
70. | Bollwein, J.,Diekmann, R.,Kaiser, M. J.,Bauer, J. M.,Uter, W.,Sieber, C. C.,Volkert, D. Distribution but not amount of protein intake is associated with frailty: A cross-sectional investigation in the region of Nürnberg. Nutrition Journal. 2013. 12:#pages# http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L52720716 10.1186/1475-2891-12-109 | X
71. | Bopp, M. J.,Houston, D. K.,Lenchik, L.,Easter, L.,Kritchevsky, S. B.,Nicklas, B. J. Lean mass loss is associated with low protein intake during dietary-induced weight loss in postmenopausal women. J Am Diet Assoc. 2008. 108:1216–20 https://www.ncbi.nlm.nih.gov/pubmed/18589032 18589032 | | | | X
72. | Bos, C.,Benamouzig, R.,Bruhat, A.,Roux, C.,Valensi, P.,Ferriere, F.,Tome, D. Nutritional status after short-term dietary supplementation in hospitalized malnourished geriatric patients. Clin Nutr. 2001. 20:225–33 https://www.ncbi.nlm.nih.gov/pubmed/11407869 11407869 | | X | | | | | | X
73. | Bossingham, M. J.,Carnell, N. S.,Campbell, W. W. Water balance, hydration status, and fat-free mass hydration in younger and older adults. Am J Clin Nutr. 2005. 81:1342–50 https://www.ncbi.nlm.nih.gov/pubmed/15941885 15941885 | | X | | X
74. | Bouchard, D. R.,Heroux, M.,Janssen, I. Association between muscle mass, leg strength, and fat mass with physical function in older adults: influence of age and sex. J Aging Health. 2011. 23:313–28 https://www.ncbi.nlm.nih.gov/pubmed/21081704 21081704 | X
75. | Bouillanne, O.,Curis, E.,Hamon-Vilcot, B.,Nicolis, I.,Chretien, P.,Schauer, N., Vincent, J. P.,Cynober, L.,Aussel, C. Impact of protein pulse feeding on lean mass in malnourished and at-risk hospitalized elderly patients: a randomized controlled trial. Clin Nutr. 2013. 32:186–92 https://www.ncbi.nlm.nih.gov/pubmed/22992307 22992307 | | X | | | | | | X
76. | Bradlee, M. L.,Mustafa, J.,Singer, M. R.,Moore, L. L. High-Protein Foods and Physical Activity Protect Against Age-Related Muscle Loss and Functional Decline. J Gerontol A Biol Sci Med Sci. 2017. 73:88–94 https://www.ncbi.nlm.nih.gov/pubmed/28549098 28549098 | | X
77. | Bradley, W. J.,Cavanagh, B. P.,Douglas, W.,Donovan, T. F.,Morton, J. P.,Close, G. L. Quantification of training load, energy intake, and physiological adaptations during a rugby preseason: a case study from an elite European rugby union squad. J Strength Cond Res. 2015. 29:534–44 https://www.ncbi.nlm.nih.gov/pubmed/25029003 25029003 | | X | | X
78. | Bray, G. A.,Redman, L. M.,de Jonge, L.,Covington, J.,Rood, J.,Brock, C.,Mancuso, S.,Martin, C. K.,Smith, S. R. Effect of protein overfeeding on energy expenditure measured in a metabolic chamber. Am J Clin Nutr. 2015. 101:496–505 https://www.ncbi.nlm.nih.gov/pubmed/25733634 25733634 | | | | X
79. | Brinkworth, G. D.,Noakes, M.,Clifton, P. M.,Buckley, J. D. Effects of a low carbohydrate weight loss diet on exercise capacity and tolerance in obese subjects. Obesity (Silver Spring). 2009. 17:1916–23 https://www.ncbi.nlm.nih.gov/pubmed/19373224 19373224 | | | | X
80. | Brown, J. C.,Harhay, M. O.,Harhay, M. N. Sarcopenia and mortality among a population-based sample of community-dwelling older adults. Journal of Cachexia, Sarcopenia and Muscle. 2015. #volume#:#pages# http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L607444252 10.1002/jcsm.12073 | | X
81. | Brown, J. C.,Harhay, M. O.,Harhay, M. N. Physical Activity, Diet Quality, and Mortality among Community-Dwelling Prefrail and Frail Older Adults. J Nutr Gerontol Geriatr. 2016. 35:253–266 https://www.ncbi.nlm.nih.gov/pubmed/27897612 27897612 | X | | | X
82. | Buch, A.,Eldor, R.,Kis, O.,Keinan-Boker, L.,Dunsky, A.,Rubin, A.,Lopez, A.,Sofer, Y.,Osher, E.,Marcus, Y.,Stern, N. The effect of circuit resistance training, empagliflozin or “vegeterranean diet” on physical and metabolic function in older subjects with type 2 diabetes: a study protocol for a randomized control trial (CEV-65 trial). BMC Geriatr. 2019. 19:228 https://www.ncbi.nlm.nih.gov/pubmed/31438863 31438863 | | | | | | | | X
83. | Buckley, C. M.,Austin, S.,Corfe, B. M.,Green, M. A.,Johnstone, A. M.,Stevenson, E. J.,Williams, E. A.,Brunstrom, J. M. Protein Valuation in Food Choice Is Positively Associated with Lean Mass in Older Adults. J Nutr. 2019. #volume#:#pages# https://www.ncbi.nlm.nih.gov/pubmed/31198945 | | | | X
84. | Budui, S.,Bigolin, F.,Giordano, F.,Leoni, S.,Berteotti, M.,Sartori, E.,Franceschini, L.,Taddei, M.,Salvetti, S.,Castiglioni, F.,Gilli, F.,Skafidas, S.,Schena, F.,Letizia Petroni, M.,Busetto, L. Effects of an intensive inpatient rehabilitation program in elderly patients with obesity. Obesity Facts. 2019. 12:199–210 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L627137592 10.1159/000497461 30928989 | X | X
85. | Burgin, J.,Nichols, S.,Dalrymple, N. The nutritional status of clinic attendees living with HIV/AIDS in St Vincent and the Grenadines. West Indian Med J. 2008. 57:438–43 https://www.ncbi.nlm.nih.gov/pubmed/19565972 19565972 | X | | | | | | | X
86. | Burke, L. M.,Hawley, J. A.,Angus, D. J.,Cox, G. R.,Clark, S. A.,Cummings, N. K., Desbrow, B.,Hargreaves, M. Adaptations to short-term high-fat diet persist during exercise despite high carbohydrate availability. Med Sci Sports Exerc. 2002. 34:83–91 https://www.ncbi.nlm.nih.gov/pubmed/11782652 11782652 | | X | | | | | | X
87. | Byam-Williams, J.,Salyer, J. Factors influencing the health-related lifestyle of community-dwelling older adults. Home Healthc Nurse. 2010. 28:115–21 https://www.ncbi.nlm.nih.gov/pubmed/20147806 20147806 | X | X | | X
88. | Callen, B. L. Nutritional screening in community dwelling older adults. Int J Older People Nurs. 2011. 6:272–81 https://www.ncbi.nlm.nih.gov/pubmed/21631876 21631876 | X | X | | X
89. | Calvani, R.,Martone, A. M.,Marzetti, E.,Onder, G.,Savera, G.,Lorenzi, M.,Serafini, E.,Bernabei, R.,Landi, F. Pre-hospital dietary intake correlates with muscle mass at the time of fracture in older hip-fractured patients. Front Aging Neurosci. 2014. 6:269 https://www.ncbi.nlm.nih.gov/pubmed/25477815 25477815 | X
90. | Campbell, B. I.,Aguilar, D.,Conlin, L.,Vargas, A.,Schoenfeld, B. J.,Corson, A.,Gai, C.,Best, S.,Galvan, E.,Couvillion, K. Effects of High Versus Low Protein Intake on Body Composition and Maximal Strength in Aspiring Female Physique Athletes Engaging in an 8-Week Resistance Training Program. Int J Sport Nutr Exerc Metab. 2018. 28:580–585 https://www.ncbi.nlm.nih.gov/pubmed/29405780 29405780 | | | | | | | | X
91. | Campbell, W. W.,Trappe, T. A.,Jozsi, A. C.,Kruskall, L. J.,Wolfe, R. R.,Evans, W. J. Dietary protein adequacy and lower body versus whole body resistive training in older humans. J Physiol. 2002. 542:631–42 https://www.ncbi.nlm.nih.gov/pubmed/12122158 12122158 | | X | X
92. | Campbell, W. W.,Trappe, T. A.,Wolfe, R. R.,Evans, W. J. The recommended dietary allowance for protein may not be adequate for older people to maintain skeletal muscle. J Gerontol A Biol Sci Med Sci. 2001. 56:M373–80 https://www.ncbi.nlm.nih.gov/pubmed/11382798 11382798 | | X | | X
93. | Cardon-Thomas, D. K.,Riviere, T.,Tieges, Z.,Greig, C. A. Dietary Protein in Older Adults: Adequate Daily Intake but Potential for Improved Distribution. Nutrients. 2017. 9:#pages# https://www.ncbi.nlm.nih.gov/pubmed/28241469 | X
94. | Cardoso, G. A.,Salgado, J. M.,Cesar Mde, C.,Donado-Pestana, C. M. The effects of green tea consumption and resistance training on body composition and resting metabolic rate in overweight or obese women. J Med Food. 2013. 16:120–7 https://www.ncbi.nlm.nih.gov/pubmed/23140132 23140132 | | X
95. | Carru, C.,Da Boit, M.,Paliogiannis, P.,Zinellu, A.,Sotgia, S.,Sibson, R.,Meakin, J. R.,Aspden, R. M.,Mangoni, A. A.,Gray, S. R. Markers of oxidative stress, skeletal muscle mass and function, and their responses to resistance exercise training in older adults. Experimental gerontology. 2018. 103:101–106 https://www.cochranelibrary.com/central/doi/10.1002/central/CN-01461497/full 29326089 | | X
96. | Carty, C. L.,Kooperberg, C.,Neuhouser, M. L.,Tinker, L.,Howard, B.,Wactawski-Wende, J.,Beresford, S. A.,Snetselaar, L.,Vitolins, M.,Allison, M.,Budrys, N., Prentice, R.,Peters, U. Low-fat dietary pattern and change in body-composition traits in the Women’s Health Initiative Dietary Modification Trial. Am J Clin Nutr. 2011. 93:516–24 https://www.ncbi.nlm.nih.gov/pubmed/21177798 21177798 | | | | X
97. | Castaneda, C.,Gordon, P. L.,Fielding, R. A.,Evans, W. J.,Crim, M. C. Marginal protein intake results in reduced plasma IGF-I levels and skeletal muscle fiber atrophy in elderly women. J Nutr Health Aging. 2000. 4:85–90 https://www.ncbi.nlm.nih.gov/pubmed/10842420 10842420 | X | X | | X
98. | Castaneda, C.,Janssen, I. Ethnic comparisons of sarcopenia and obesity in diabetes. Ethn Dis. 2005. 15:664–70 https://www.ncbi.nlm.nih.gov/pubmed/16259491 16259491 | X | X | | X
99. | Catapano, G.,Pedone, C.,Nunziata, E.,Zizzo, A.,Passantino, A.,Incalzi, R. A. Nutrient intake and serum cytokine pattern in elderly people with heart failure. Eur J Heart Fail. 2008. 10:428–34 https://www.ncbi.nlm.nih.gov/pubmed/18353717 18353717 | X | X | | X | | | | X
100. | Cervo, M. M.,Shivappa, N.,Hebert, J. R.,Oddy, W. H.,Winzenberg, T.,Balogun, S., Wu, F.,Ebeling, P.,Aitken, D.,Jones, G.,Scott, D. Longitudinal associations between dietary inflammatory index and musculoskeletal health in community-dwelling older adults. Clin Nutr. 2019. #volume#:#pages# https://www.ncbi.nlm.nih.gov/pubmed/30852031 | | | | X
101. | Cesari, M.,Pahor, M.,Bartali, B.,Cherubini, A.,Penninx, B. W.,Williams, G. R., Atkinson, H.,Martin, A.,Guralnik, J. M.,Ferrucci, L. Antioxidants and physical performance in elderly persons: the Invecchiare in Chianti (InCHIANTI) study. Am J Clin Nutr. 2004. 79:289–94 https://www.ncbi.nlm.nih.gov/pubmed/14749236 14749236 | X
102. | Chan, R.,Leung, J.,Woo, J.,Kwok, T. Associations of dietary protein intake on subsequent decline in muscle mass and physical functions over four years in ambulant older Chinese people. J Nutr Health Aging. 2014. 18:171–7 https://www.ncbi.nlm.nih.gov/pubmed/24522470 24522470 | | X
103. | Chaput, J. P.,Lord, C.,Cloutier, M.,Aubertin Leheudre, M.,Goulet, E. D.,Rousseau, S.,Khalil, A.,Dionne, I. J. Relationship between antioxidant intakes and class I sarcopenia in elderly men and women. J Nutr Health Aging. 2007. 11:363–9 https://www.ncbi.nlm.nih.gov/pubmed/17653501 17653501 | | X
104. | Charlton, K.,Walton, K.,Batterham, M.,Brock, E.,Langford, K.,McMahon, A.,Roodenrys, S.,Koh, F.,Host, A.,Crowe, R.,Thornhill, K. Pork and Chicken Meals Similarly Impact on Cognitive Function and Strength in Community-Living Older Adults: A Pilot Study. J Nutr Gerontol Geriatr. 2016. 35:124–45 https://www.ncbi.nlm.nih.gov/pubmed/27153252 27153252 | | X
105. | Chevalier, S.,Gougeon, R.,Nayar, K.,Morais, J. A. Frailty amplifies the effects of aging on protein metabolism: role of protein intake. Am J Clin Nutr. 2003. 78:422–9 https://www.ncbi.nlm.nih.gov/pubmed/12936924 12936924 | | | | X
106. | Chiang, P. H.,Wahlqvist, M. L.,Huang, L. Y.,Chang, Y. C. Leisure time physical activities and dietary quality of the general and indigenous Taiwanese populations are associated with fat distribution and sarcopenia. Asia Pac J Clin Nutr. 2013. 22:599–613 https://www.ncbi.nlm.nih.gov/pubmed/24231021 24231021 | X | | X
107. | Chin, A. Paw M. J.,de Jong, N.,Schouten, E. G.,Hiddink, G. J.,Kok, F. J. Physical exercise and/or enriched foods for functional improvement in frail, independently living elderly: a randomized controlled trial. Arch Phys Med Rehabil. 2001. 82:811–7 https://www.ncbi.nlm.nih.gov/pubmed/11387588 11387588 | | X
108. | Choi, H. R.,Kim, J.,Lim, H.,Park, Y. K. Two-Week Exclusive Supplementation of Modified Ketogenic Nutrition Drink Reserves Lean Body Mass and Improves Blood Lipid Profile in Obese Adults: A Randomized Clinical Trial. Nutrients. 2018. 10:#pages# https://www.ncbi.nlm.nih.gov/pubmed/30513970 | | X
109. | Chomentowski, P.,Dube, J. J.,Amati, F.,Stefanovic-Racic, M.,Zhu, S.,Toledo, F. G., Goodpaster, B. H. Moderate exercise attenuates the loss of skeletal muscle mass that occurs with intentional caloric restriction-induced weight loss in older, overweight to obese adults. J Gerontol A Biol Sci Med Sci. 2009. 64:575–80 https://www.ncbi.nlm.nih.gov/pubmed/19276190 19276190 | | X
110. | Chun, B. O.,Yun, M. E.,Kim, I. M.,Lee, J. K. Effects of short-term training camp including aerobic exercise and vegetarian diet on body composition, physical fitness and blood biochemical parameters in collegians. Gazzetta Medica Italiana Archivio per le Scienze Mediche. 2017. 176:289–298 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L615773809 10.23736/S0393-3660.16.03277-0 | | | | | | | | X
111. | Clamp, L. D.,Hume, D. J.,Lambert, E. V.,Kroff, J. Successful and unsuccessful weight-loss maintainers: strategies to counteract metabolic compensation following weight loss. J Nutr Sci. 2018. 7:e20 https://www.ncbi.nlm.nih.gov/pubmed/29988905 29988905 | X
112. | Cliffe, M.,Bloodworth, L. L.,Jibani, M. M. Can malnutrition in predialysis patients be prevented by dietetic intervention?. J Ren Nutr. 2001. 11:161–5 https://www.ncbi.nlm.nih.gov/pubmed/11466667 11466667 | | | | | | | | X
113. | Coelho-Junior, H. J.,Calvani, R.,Goncalves, I. O.,Rodrigues, B.,Picca, A.,Landi, F., Bernabei, R.,Uchida, M. C.,Marzetti, E. High relative consumption of vegetable protein is associated with faster walking speed in well-functioning older adults. Aging Clin Exp Res. 2019. #volume#:#pages# https://www.ncbi.nlm.nih.gov/pubmed/31115875 | X
114. | Coin, A.,Perissinotto, E.,Enzi, G.,Zamboni, M.,Inelmen, E. M.,Frigo, A. C.,Manzato, E.,Busetto, L.,Buja, A.,Sergi, G. Predictors of low bone mineral density in the elderly: the role of dietary intake, nutritional status and sarcopenia. Eur J Clin Nutr. 2008. 62:802–9 https://www.ncbi.nlm.nih.gov/pubmed/17637603 17637603 | X | X
115. | Coin, A.,Sergi, G.,Beninca, P.,Lupoli, L.,Cinti, G.,Ferrara, L.,Benedetti, G.,Tomasi, G.,Pisent, C.,Enzi, G. Bone mineral density and body composition in underweight and normal elderly subjects. Osteoporos Int. 2000. 11:1043–50 https://www.ncbi.nlm.nih.gov/pubmed/11256896 11256896 | X | X
116. | Coker, R. H.,Miller, S.,Schutzler, S.,Deutz, N.,Wolfe, R. R. Whey protein and essential amino acids promote the reduction of adipose tissue and increased muscle protein synthesis during caloric restriction-induced weight loss in elderly, obese individuals. Nutrition journal. 2012. 11:#pages# https://www.cochranelibrary.com/central/doi/10.1002/central/CN-00912677/full | | X
117. | Colica, C.,Merra, G.,Gasbarrini, A.,De Lorenzo, A.,Cioccoloni, G.,Gualtieri, P., Perrone, M. A.,Bernardini, S.,Bernardo, V.,Di Renzo, L.,Marchetti, M. Efficacy and safety of very-low-calorie ketogenic diet: a double blind randomized crossover study. Eur Rev Med Pharmacol Sci. 2017. 21:2274–2289 https://www.ncbi.nlm.nih.gov/pubmed/28537652 28537652 | X | | X
118. | Confortin, S. C.,Ono, L. M.,Barbosa, A. R.,d’Orsi, E. Sarcopenia and its association with changes in socioeconomic, behavioral, and health factors: the EpiFloripa Elderly Study. Cadernos de saude publica. 2018. 34:e00164917 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L626975474 10.1590/0102-311X00164917 30517315 | | X
119. | Cooke, M. B.,Brabham, B.,Buford, T. W.,Shelmadine, B. D.,McPheeters, M., Hudson, G. M.,Stathis, C.,Greenwood, M.,Kreider, R.,Willoughby, D. S. Creatine supplementation post-exercise does not enhance training-induced adaptations in middle to older aged males. Eur J Appl Physiol. 2014. 114:1321–32 https://www.ncbi.nlm.nih.gov/pubmed/24633488 24633488 | | X
120. | Coulson, C. E.,Williams, L. J.,Brennan, S. L.,Berk, M.,Kotowicz, M. A.,Lubman, D. I.,Pasco, J. A. Alcohol consumption and body composition in a population-based sample of elderly Australian men. Aging Clin Exp Res. 2013. 25:183–92 https://www.ncbi.nlm.nih.gov/pubmed/23739904 23739904 | | X
121. | Cramer, J. T.,Cruz-Jentoft, A. J.,Landi, F.,Hickson, M.,Zamboni, M.,Pereira, S. L., Hustead, D. S.,Mustad, V. A. Impacts of High-Protein Oral Nutritional Supplements Among Malnourished Men and Women with Sarcopenia: A Multicenter, Randomized, Double-Blinded, Controlled Trial. J Am Med Dir Assoc. 2016. 17:1044–1055 https://www.ncbi.nlm.nih.gov/pubmed/27780567 27780567 | | X
122. | Cresci, B.,Pala, L.,Poggiali, R.,Guarnieri, C.,Mannucci, E.,Bigiarini, M.,Rotella, C. M. False and true pre-treatment predictors of weight loss in obese patients starting a program for lifestyle change. Eat Weight Disord. 2014. 19:489–94 https://www.ncbi.nlm.nih.gov/pubmed/24816471 24816471 | | X | | X
123. | Crown, A. L.,Cottle, K.,Lightman, S. L.,Falk, S.,Mohamed-Ali, V.,Armstrong, L., Millar, A. B.,Holly, J. M. What is the role of the insulin-like growth factor system in the pathophysiology of cancer cachexia, and how is it regulated?. Clin Endocrinol (Oxf). 2002. 56:723–33 https://www.ncbi.nlm.nih.gov/pubmed/12072041 12072041 | X | X | | X | | | | X
124. | Cupisti, A.,Licitra, R.,Chisari, C.,Stampacchia, G.,D’Alessandro, C.,Galetta, F., Rossi, B.,Barsotti, G. Skeletal muscle and nutritional assessment in chronic renal failure patients on a protein-restricted diet. J Intern Med. 2004. 255:115–24 https://www.ncbi.nlm.nih.gov/pubmed/14687247 14687247 | | X | | | | | | X
125. | D’Angelo, E.,Di Blasio, A.,Di Donato, F.,Di Gregorio, S.,Di Renzo, D.,Ripari, P. Relationships between physical exercise practice, dietary behaviour and body composition in female university students. J Sports Med Phys Fitness. 2010. 50:311–7 https://www.ncbi.nlm.nih.gov/pubmed/20842092 20842092 | | X | | X | | | | X
126. | da Silva, A. P.,Valente, A.,Chaves, C.,Matos, A.,Gil, A.,Santos, A. C.,Gorjao-Clara, J. P.,Bicho, M. Characterization of Portuguese Centenarian Eating Habits, Nutritional Biomarkers, and Cardiovascular Risk: A Case Control Study. Oxid Med Cell Longev. 2018. 2018:5296168 https://www.ncbi.nlm.nih.gov/pubmed/29725498 29725498 | | X
127. | Daly, R. M.,O’Connell, S. L.,Mundell, N. L.,Grimes, C. A.,Dunstan, D. W.,Nowson, C. A. Protein-enriched diet, with the use of lean red meat, combined with progressive resistance training enhances lean tissue mass and muscle strength and reduces circulating IL-6 concentrations in elderly women: A cluster randomized controlled trial. American Journal of Clinical Nutrition. 2014. 99:899–910 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L372703709 10.3945/ajcn.113.064154 | | X
128. | Dalzill, C.,Nigam, A.,Juneau, M.,Guilbeault, V.,Latour, E.,Mauriege, P.,Gayda, M. Intensive lifestyle intervention improves cardiometabolic and exercise parameters in metabolically healthy obese and metabolically unhealthy obese individuals. Can J Cardiol. 2014. 30:434–40 https://www.ncbi.nlm.nih.gov/pubmed/24561010 24561010 | | X
129. | Dandanell, S.,Skovborg, C.,Praest, C. B.,Kristensen, K. B.,Nielsen, M. G.,Lionett, S.,Jorgensen, S. D.,Vigelso, A.,Dela, F.,Helge, J. W. Maintaining a clinical weight loss after intensive lifestyle intervention is the key to cardiometabolic health. Obes Res Clin Pract. 2017. 11:489–498 https://www.ncbi.nlm.nih.gov/pubmed/27720417 27720417 | | X
130. | Daskalopoulou, C.,Koukounari, A.,Ayuso-Mateos, J. L.,Prince, M.,Prina, A. M. Associations of Lifestyle Behaviour and Healthy Ageing in Five Latin American and the Caribbean Countries-A 10/66 Population-Based Cohort Study. Nutrients. 2018. 10:#pages# https://www.ncbi.nlm.nih.gov/pubmed/30380734 | | X | | X
131. | De Hoogh, I.,Doets, E.,Holthuysen, N.,Wopereis, S.,Verain, M.,Boorsma, A., Bouwman, E.,Pasman, W.,Van Erk, M.,Reinders, M. Beneficial effect of personalised lifestyle advice as compared to generic advice on wellbeing among active dutch seniors-a pilot study. Annals of nutrition & metabolism. 2017. 71:456–457 https://www.cochranelibrary.com/central/doi/10.1002/central/CN-01428951/full | | | | | X
132. | de Luis, D. A.,Aller, R.,Izaola, O.,Gonzalez Sagrado, M.,Conde, R. Resting energy expenditure, cardiovascular risk factors and insulin resistance in obese patients. Ann Nutr Metab. 2005. 49:381–5 https://www.ncbi.nlm.nih.gov/pubmed/16219989 16219989 | | X | | X
133. | de Oliveira, E. P.,McLellan, K. C.,Vaz de Arruda Silveira, L.,Burini, R. C. Dietary factors associated with metabolic syndrome in Brazilian adults. Nutr J. 2012. 11:13 https://www.ncbi.nlm.nih.gov/pubmed/22417631 22417631 | X | X | | X
134. | de Oliveira, E. P.,Moreto, F.,Silveira, L. V.,Burini, R. C. Dietary, anthropometric, and biochemical determinants of uric acid in free-living adults. Nutr J. 2013. 12:11 https://www.ncbi.nlm.nih.gov/pubmed/23311699 23311699 | X
135. | de Souza Genaro, P.,de Medeiros Pinheiro, M.,Szejnfeld, V. L.,Martini, L. A. Secondary hyperparathyroidism and its relationship with sarcopenia in elderly women. Arch Gerontol Geriatr. 2015. 60:349–53 https://www.ncbi.nlm.nih.gov/pubmed/25614177 25614177 | | X
136. | Dehail, P.,Joseph, P. A.,Faux, P.,Rainfray, M.,Emeriau, J. P.,Barat, M.,Bourdel-Marchasson, I. Early changes in isokinetic lower limb muscle strength in recovering geriatric subjects on the basis of nutritional status. J Nutr Health Aging. 2005. 9:356–63 https://www.ncbi.nlm.nih.gov/pubmed/16222403 16222403 | | X | | | | | | X
137. | Deibert, P.,Konig, D.,Schmidt-Trucksaess, A.,Zaenker, K. S.,Frey, I.,Landmann, U., Berg, A. Weight loss without losing muscle mass in pre-obese and obese subjects induced by a high-soy-protein diet. Int J Obes Relat Metab Disord. 2004. 28:1349–52 https://www.ncbi.nlm.nih.gov/pubmed/15303108 15303108 | | X
138. | Demling, R. H.,DeSanti, L. Effect of a hypocaloric diet, increased protein intake and resistance training on lean mass gains and fat mass loss in overweight police officers. Ann Nutr Metab. 2000. 44:21–9 https://www.ncbi.nlm.nih.gov/pubmed/10838463 10838463 | | X
139. | Denissen, K. F.,Janssen, L. M.,Eussen, S. J.,van Dongen, M. C.,Wijckmans, N. E., van Deurse, N. D.,Dagnelie, P. C. Delivery of Nutritious Meals to Elderly Receiving Home Care: Feasibility and Effectiveness. J Nutr Health Aging. 2017. 21:370–380 https://www.ncbi.nlm.nih.gov/pubmed/28346563 28346563 | | X
140. | Deriemaeker, P.,Aerenhouts, D.,De Ridder, D.,Hebbelinck, M.,Clarys, P. Health aspects, nutrition and physical characteristics in matched samples of institutionalized vegetarian and non-vegetarian elderly (> 65yrs). Nutr Metab (Lond). 2011. 8:37 https://www.ncbi.nlm.nih.gov/pubmed/21672249 21672249 | X
141. | Deutz, N. E. P.,Thaden, J. J.,Ten Have, G. A. M.,Walker, D. K.,Engelen, Mpkj Metabolic phenotyping using kinetic measurements in young and older healthy adults. Metabolism. 2018. 78:167–178 https://www.ncbi.nlm.nih.gov/pubmed/28986165 28986165 | | X
142. | Dhonukshe-Rutten, R. A. M.,Van De Rest, O.,Tieland, M. Nutrition later in life: for bone, brain and muscle function. European geriatric medicine. 2014. 5:S41- https://www.cochranelibrary.com/central/doi/10.1002/central/CN-01023539/full | | | | | X
143. | Dias, F. M.,Costa, S. O.,Pereira de Freitas, J.,Pinto Ada, C.,Vigario Pdos, S., Mainenti, M. R. Functional Capacity of Oldest Old Living in a Long-stay Institution in Rio De Janeiro, Brazil. J Phys Ther Sci. 2014. 26:1097–105 https://www.ncbi.nlm.nih.gov/pubmed/25140105 25140105 | X
144. | Dipla, K.,Makri, M.,Zafeiridis, A.,Soulas, D.,Tsalouhidou, S.,Mougios, V.,Kellis, S. An isoenergetic high-protein, moderate-fat diet does not compromise strength and fatigue during resistance exercise in women. Br J Nutr. 2008. 100:283–6 https://www.ncbi.nlm.nih.gov/pubmed/18618943 18618943 | | X | | X
145. | Dirks, M. L.,Wall, B. T.,Kramer, I. F.,Zorenc, A. H.,Goessens, J. P.,Gijsen, A. P.,van Loon, L. J. A single session of neuromuscular electrical stimulation does not augment postprandial muscle protein accretion. Am J Physiol Endocrinol Metab. 2016. 311:E278–85 https://www.ncbi.nlm.nih.gov/pubmed/27279248 27279248 | | X
146. | Doets, E. L.,de Hoogh, I. M.,Holthuysen, N.,Wopereis, S.,Verain, M. C. D.,van den Puttelaar, J.,Hogenelst, K.,Boorsma, A.,Bouwman, E. P.,Timmer, M.,Pasman, W. J.,van Erk, M.,Reinders, M. J. Beneficial effect of personalized lifestyle advice compared to generic advice on wellbeing among Dutch seniors - An explorative study. Physiol Behav. 2019. 210:112642 https://www.ncbi.nlm.nih.gov/pubmed/31394106 31394106 | | | | X
147. | Donaldson, M. S.,Speight, N.,Loomis, S. Fibromyalgia syndrome improved using a mostly raw vegetarian diet: an observational study. BMC Complement Altern Med. 2001. 1:7 https://www.ncbi.nlm.nih.gov/pubmed/11602026 11602026 | X | X | | X
148. | Doubova, S. V.,Sanchez-Garcia, S.,Infante-Castaneda, C.,Perez-Cuevas, R. Factors associated with regular physical exercise and consumption of fruits and vegetables among Mexican older adults. BMC Public Health. 2016. 16:952 https://www.ncbi.nlm.nih.gov/pubmed/27612444 27612444 | X
149. | Draganidis, D.,Jamurtas, A. Z.,Stampoulis, T.,Laschou, V. C.,Deli, C. K., Georgakouli, K.,Papanikolaou, K.,Chatzinikolaou, A.,Michalopoulou, M., Papadopoulos, C.,Tsimeas, P.,Chondrogianni, N.,Koutedakis, Y.,Karagounis, L. G., Fatouros, I. G. Disparate Habitual Physical Activity and Dietary Intake Profiles of Elderly Men with Low and Elevated Systemic Inflammation. Nutrients. 2018. 10:#pages# https://www.ncbi.nlm.nih.gov/pubmed/29734698 | X | X
150. | Drew, L. Fighting the inevitability of ageing. Nature. 2018. 555:S15–s17 https://www.ncbi.nlm.nih.gov/pubmed/29517046 | X | | | | X
151. | Drks, Prevention of malnutrition and sarcopenia in aging people with proteindrinks. Http://www.who.int/trialsearch/trial2.aspx? Trialid=drks00012273. 2017. #volume#:#pages# https://www.cochranelibrary.com/central/doi/10.1002/central/CN-01889119/full | X | X
152. | Duhamel, T. A.,Green, H. J.,Perco, J. G.,Ouyang, J. Comparative effects of a low-carbohydrate diet and exercise plus a low-carbohydrate diet on muscle sarcoplasmic reticulum responses in males. Am J Physiol Cell Physiol. 2006. 291:C607–17 https://www.ncbi.nlm.nih.gov/pubmed/16707551 16707551 | | | | X
153. | Duhamel, T. A.,Perco, J. G.,Green, H. J. Manipulation of dietary carbohydrates after prolonged effort modifies muscle sarcoplasmic reticulum responses in exercising males. Am J Physiol Regul Integr Comp Physiol. 2006. 291:R1100–10 https://www.ncbi.nlm.nih.gov/pubmed/16690765 16690765 | | | | X
154. | Dulac, M. C.,Pion, C. H.,Lemieux, F.,Boutros El Hajj, G.,Belanger, M.,Gaudreau, P.,Chevalier, S.,Morais, J. A.,Gouspillou, G.,Aubertin-Leheudre, M. Differences in muscle adaptation to a 12-week mixed power training in elderly men, depending on usual protein intake. Exp Gerontol. 2018. 104:78–85 https://www.ncbi.nlm.nih.gov/pubmed/29421607 29421607 | | X
155. | Dziuba-Słonina, A.,Rywacka, A.,Kołodziej, M. Changes in quadriceps muscle girth after anterior cruciate ligament injury followed by electrostimulation combined with high protein diet and exercises (ARPwave method). Physiotherapy Quarterly. 2018. 26:21–26 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L622973603 10.5114/pq.2018.74703 | X | X | | X | | | | X
156. | Edholm, P.,Strandberg, E.,Kadi, F. Lower limb explosive strength capacity in elderly women: effects of resistance training and healthy diet. J Appl Physiol (1985). 2017. 123:190–196 https://www.ncbi.nlm.nih.gov/pubmed/28473614 28473614 | | X
157. | Farham, B. Family meals and old age. S Afr Med J. 2006. 96:606, 608 https://www.ncbi.nlm.nih.gov/pubmed/16958164 | X
158. | Farina, E. K.,Thompson, L. A.,Knapik, J. J.,Pasiakos, S. M.,Lieberman, H. R.,McClung, J. P. Diet Quality Is Associated with Physical Performance and Special Forces Selection. Med Sci Sports Exerc. 2019. #volume#:#pages# https://www.ncbi.nlm.nih.gov/pubmed/31436735 | | | | X
159. | Farsijani, S.,Morais, J. A.,Payette, H.,Gaudreau, P.,Shatenstein, B.,Gray-Donald, K.,Chevalier, S. Relation between mealtime distribution of protein intake and lean mass loss in free-living older adults of the NuAge study. Am J Clin Nutr. 2016. 104:694–703 https://www.ncbi.nlm.nih.gov/pubmed/27465379 27465379 | | | | X
160. | Farsijani, S.,Payette, H.,Morais, J. A.,Shatenstein, B.,Gaudreau, P.,Chevalier, S. Even mealtime distribution of protein intake is associated with greater muscle strength, but not with 3-y physical function decline, in free-living older adults: the Quebec longitudinal study on Nutrition as a Determinant of Successful Aging (NuAge study). Am J Clin Nutr. 2017. 106:113–124 https://www.ncbi.nlm.nih.gov/pubmed/28515070 28515070 | | X
161. | Ferland, A.,Chateau-Degat, M. L.,Hernandez, T. L.,Eckel, R. H. Tissue-specific responses of lipoprotein lipase to dietary macronutrient composition as a predictor of weight gain over 4 years. Obesity (Silver Spring). 2012. 20:1006–11 https://www.ncbi.nlm.nih.gov/pubmed/22262159 22262159 | | | | X
162. | Ferrand, C.,Feart, C.,Martinent, G.,Albinet, C.,Andre, N.,Audiffren, M. Dietary patterns in French home-living older adults: Results from the PRAUSE study. Arch Gerontol Geriatr. 2017. 70:180–185 https://www.ncbi.nlm.nih.gov/pubmed/28192753 28192753 | X
163. | Ferrier, K. E.,Nestel, P.,Taylor, A.,Drew, B. G.,Kingwell, B. A. Diet but not aerobic exercise training reduces skeletal muscle TNF-alpha in overweight humans. Diabetologia. 2004. 47:630–7 https://www.ncbi.nlm.nih.gov/pubmed/15298339 15298339 | | X | | X
164. | Fiatarone Singh, M. A.,Bernstein, M. A.,Ryan, A. D.,O’Neill, E. F.,Clements, K. M., Evans, W. J. The effect of oral nutritional supplements on habitual dietary quality and quantity in frail elders. J Nutr Health Aging. 2000. 4:5–12 https://www.ncbi.nlm.nih.gov/pubmed/10828934 10828934 | | X
165. | Fitzgerald, J. S.,Peterson, B. J.,Wilson, P. B.,Rhodes, G. S.,Ingraham, S. J. Vitamin D status is associated with adiposity in male ice hockey players. Med Sci Sports Exerc. 2015. 47:655–61 https://www.ncbi.nlm.nih.gov/pubmed/24983343 24983343 | X | X | | X | | | | X
166. | Ford, D. W.,Jensen, G. L.,Still, C.,Wood, C.,Mitchell, D. C.,Erickson, P.,Bailey, R., Smiciklas-Wright, H.,Coffman, D. L.,Hartman, T. J. The associations between diet quality, Body Mass Index (BMI) and Health and Activity Limitation Index (HALex) in the Geisinger Rural Aging Study (GRAS). J Nutr Health Aging. 2014. 18:167–70 https://www.ncbi.nlm.nih.gov/pubmed/24522469 24522469 | | | | X
167. | Foscolou, A.,Koloverou, E.,Matalas, A. L.,Tyrovolas, S.,Chrysohoou, C.,Sidossis, L.,Rallidis, L.,Panagiotakos, D. B. Decomposition of Mediterranean Dietary Pattern on Successful Aging, Among Older Adults: A Combined Analysis of Two Epidemiological Studies. J Aging Health. 2019. 31:1549–1567 https://www.ncbi.nlm.nih.gov/pubmed/29938559 29938559 | X
168. | Foscolou, A.,Magriplis, E.,Tyrovolas, S.,Soulis, G.,Bountziouka, V.,Mariolis, A., Piscopo, S.,Valacchi, G.,Anastasiou, F.,Gotsis, E.,Metallinos, G.,Tyrovola, D.,Polystipioti, A.,Polychronopoulos, E.,Matalas, A. L.,Lionis, C.,Zeimbekis, A.,Tur, J. A.,Sidossis, L. S.,Panagiotakos, D. Lifestyle determinants of healthy ageing in a Mediterranean population: The multinational MEDIS study. Exp Gerontol. 2018. 110:35–41 https://www.ncbi.nlm.nih.gov/pubmed/29763722 29763722 | X
169. | Fougere, B.,Mazzuco, S.,Spagnolo, P.,Guyonnet, S.,Vellas, B.,Cesari, M.,Gallucci, M. Association between the Mediterranean-style Dietary Pattern Score and Physical Performance: Results from TRELONG Study. J Nutr Health Aging. 2016. 20:415–9 https://www.ncbi.nlm.nih.gov/pubmed/26999242 26999242 | X
170. | Franzon, K.,Byberg, L.,Sjogren, P.,Zethelius, B.,Cederholm, T.,Kilander, L. Predictors of Independent Aging and Survival: A 16-Year Follow-Up Report in Octogenarian Men. J Am Geriatr Soc. 2017. 65:1953–1960 https://www.ncbi.nlm.nih.gov/pubmed/28685810 28685810 | | | | X
171. | Frassetto, L. A.,Morris, R. C., Jr.,Sellmeyer, D. E.,Sebastian, A. Adverse effects of sodium chloride on bone in the aging human population resulting from habitual consumption of typical American diets. J Nutr. 2008. 138:419s–422s https://www.ncbi.nlm.nih.gov/pubmed/18203914 18203914 | X
172. | Fritzen, A. M.,Lundsgaard, A. M.,Jordy, A. B.,Poulsen, S. K.,Stender, S.,Pilegaard, H.,Astrup, A.,Larsen, T. M.,Wojtaszewski, J. F.,Richter, E. A.,Kiens, B. New Nordic Diet-Induced Weight Loss Is Accompanied by Changes in Metabolism and AMPK Signaling in Adipose Tissue. J Clin Endocrinol Metab. 2015. 100:3509–19 https://www.ncbi.nlm.nih.gov/pubmed/26126206 26126206 | | | | X
173. | Fukuda, Y.,Yamamoto, K.,Hirao, M.,Nishikawa, K.,Nagatsuma, Y.,Nakayama, T., Tanikawa, S.,Maeda, S.,Uemura, M.,Miyake, M.,Hama, N.,Miyamoto, A.,Ikeda, M., Nakamori, S.,Sekimoto, M.,Fujitani, K.,Tsujinaka, T. Sarcopenia is associated with severe postoperative complications in elderly gastric cancer patients undergoing gastrectomy. Gastric Cancer. 2016. 19:986–93 https://www.ncbi.nlm.nih.gov/pubmed/26407875 26407875 | | X | | | | | | X
174. | Galbreath, M.,Campbell, B.,LaBounty, P.,Bunn, J.,Dove, J.,Harvey, T.,Hudson, G.,Gutierrez, J. L.,Levers, K.,Galvan, E.,Jagim, A.,Greenwood, L.,Cooke, M. B.,Greenwood, M.,Rasmussen, C.,Kreider, R. B. Effects of Adherence to a Higher Protein Diet on Weight Loss, Markers of Health, and Functional Capacity in Older Women Participating in a Resistance-Based Exercise Program. Nutrients. 2018. 10:#pages# https://www.ncbi.nlm.nih.gov/pubmed/30103509 | | X
175. | Gale, C. R.,Martyn, C. N.,Kellingray, S.,Eastell, R.,Cooper, C. Intrauterine programming of adult body composition. J Clin Endocrinol Metab. 2001. 86:267–72 https://www.ncbi.nlm.nih.gov/pubmed/11232011 11232011 | | X
176. | Galesi, L. F.,Leandro-Merhi, V. A.,de Oliveira, M. R. Association between indicators of dementia and nutritional status in institutionalised older people. Int J Older People Nurs. 2013. 8:236–43 https://www.ncbi.nlm.nih.gov/pubmed/22394646 22394646 | | X | | X | | | | X
177. | Gallucci, M.,Mazzuco, S.,Ongaro, F.,Di Giorgi, E.,Mecocci, P.,Cesari, M.,Albani, D., Forloni, G. L.,Durante, E.,Gajo, G. B.,Zanardo, A.,Siculi, M.,Caberlotto, L.,Regini, C. Body mass index, lifestyles, physical performance and cognitive decline: the “Treviso Longeva (TRELONG)” study. J Nutr Health Aging. 2013. 17:378–84 https://www.ncbi.nlm.nih.gov/pubmed/23538662 23538662 | | | | X
178. | Gallucci, M.,Pallucca, C.,Di Battista, M. E.,Fougereand, B.,Grossi, E. Artificial Neural Networks Help to Better Understand the Interplay Between Cognition, Mediterranean Diet, and Physical Performance: Clues from TRELONG Study. J Alzheimers Dis. 2019. #volume#:#pages# https://www.ncbi.nlm.nih.gov/pubmed/31524170 | | | | X
179. | Garduno-Diaz, S. D.,Khokhar, S. South Asian dietary patterns and their association with risk factors for the metabolic syndrome. J Hum Nutr Diet. 2013. 26:145–55 https://www.ncbi.nlm.nih.gov/pubmed/22943473 | X | | | X
180. | Garthe, I.,Raastad, T.,Refsnes, P. E.,Sundgot-Borgen, J. Effect of nutritional intervention on body composition and performance in elite athletes. Eur J Sport Sci. 2013. 13:295–303 https://www.ncbi.nlm.nih.gov/pubmed/23679146 23679146 | | | | | | | | X
181. | Gazzani, D.,Zamboni, F.,Spelta, F.,Ferrari, P.,Mattioli, V.,Cazzoletti, L.,Zanolin, E., Tardivo, S.,Ferrari, M. Vegetable but not animal protein intake is associated to a better physical performance: a study on a general population sample of adults. Food Nutr Res. 2019. 63:#pages# https://www.ncbi.nlm.nih.gov/pubmed/31565042 | X | | | X
182. | Geerling, B. J.,Badart-Smook, A.,Stockbrugger, R. W.,Brummer, R. J. Comprehensive nutritional status in recently diagnosed patients with inflammatory bowel disease compared with population controls. Eur J Clin Nutr. 2000. 54:514–21 https://www.ncbi.nlm.nih.gov/pubmed/10878655 10878655 | X | X | | X
183. | Geirsdottir, O. G.,Arnarson, A.,Ramel, A.,Jonsson, P. V.,Thorsdottir, I. Dietary protein intake is associated with lean body mass in community-dwelling older adults. Nutr Res. 2013. 33:608–12 https://www.ncbi.nlm.nih.gov/pubmed/23890349 23890349 | X
184. | Genaro Pde, S.,Pinheiro Mde, M.,Szejnfeld, V. L.,Martini, L. A. Dietary protein intake in elderly women: association with muscle and bone mass. Nutr Clin Pract. 2015. 30:283–9 https://www.ncbi.nlm.nih.gov/pubmed/25107954 25107954 | X
185. | Germain, L.,Latarche, C.,Kesse-Guyot, E.,Galan, P.,Hercberg, S.,Briancon, S. Does compliance with nutrition guidelines lead to healthy aging? A quality-of-life approach. J Acad Nutr Diet. 2013. 113:228-40.e1–2 https://www.ncbi.nlm.nih.gov/pubmed/23351626 23351626 | | | | X
186. | Ghloum, K.,Hajji, S. Comparison of diet consumption, body composition and lipoprotein lipid values of Kuwaiti fencing players with international norms. J Int Soc Sports Nutr. 2011. 8:13 https://www.ncbi.nlm.nih.gov/pubmed/21992447 21992447 | X
187. | Gillen, J. B.,Trommelen, J.,Wardenaar, F. C.,Brinkmans, N. Y.,Versteegen, J. J., Jonvik, K. L.,Kapp, C.,de Vries, J.,van den Borne, J. J.,Gibala, M. J.,van Loon, L. J. Dietary Protein Intake and Distribution Patterns of Well-Trained Dutch Athletes. Int J Sport Nutr Exerc Metab. 2017. 27:105–114 https://www.ncbi.nlm.nih.gov/pubmed/27710150 27710150 | X
188. | Gingrich, A.,Rennekamp, R.,Brandl, B.,Skurk, T.,Hauner, H.,Sieber, C. C.,Volkert, D.,Kiesswetter, E. Do Aspects of Protein Intake Vary Across the Week in Healthy Community-Dwelling Older Adults?-An enable Study. Nutrients. 2018. 10:#pages# https://www.ncbi.nlm.nih.gov/pubmed/30177590 | X
189. | Gjevestad, G. O.,Ottestad, I.,Biong, A. S.,Iversen, P. O.,Retterstol, K.,Raastad, T., Skalhegg, B. S.,Ulven, S. M.,Holven, K. B. Consumption of protein-enriched milk has minor effects on inflammation in older adults-A 12-week double-blind randomized controlled trial. Mech Ageing Dev. 2017. 162:1–8 https://www.ncbi.nlm.nih.gov/pubmed/28163108 28163108 | | X
190. | Glabska, D.,Cackowska, K.,Guzek, D. Comparison of the Body Composition of Caucasian Young Normal Body Mass Women, Measured in the Follicular Phase, Depending on the Carbohydrate Diet Level. Medicina (Kaunas). 2018. 54:#pages# https://www.ncbi.nlm.nih.gov/pubmed/30563184 | X | | | X
191. | Goff, L. M.,Bell, J. D.,So, P. W.,Dornhorst, A.,Frost, G. S. Veganism and its relationship with insulin resistance and intramyocellular lipid. Eur J Clin Nutr. 2005. 59:291–8 https://www.ncbi.nlm.nih.gov/pubmed/15523486 15523486 | X | | | X
192. | Gojda, J.,Patkova, J.,Jacek, M.,Potockova, J.,Trnka, J.,Kraml, P.,Andel, M. Higher insulin sensitivity in vegans is not associated with higher mitochondrial density. Eur J Clin Nutr. 2013. 67:1310–5 https://www.ncbi.nlm.nih.gov/pubmed/24149445 24149445 | X | | | X
193. | Gomez-Arbelaez, D.,Bellido, D.,Castro, A. I.,Ordonez-Mayan, L.,Carreira, J., Galban, C.,Martinez-Olmos, M. A.,Crujeiras, A. B.,Sajoux, I.,Casanueva, F. F. Body Composition Changes After Very-Low-Calorie Ketogenic Diet in Obesity Evaluated by 3 Standardized Methods. J Clin Endocrinol Metab. 2017. 102:488–498 https://www.ncbi.nlm.nih.gov/pubmed/27754807 27754807 | X
194. | Gonzalez-Reimers, E.,Alvisa-Negrin, J.,Santolaria-Fernandez, F.,Candelaria Martin-Gonzalez, M.,Hernandez-Betancor, I.,Fernandez-Rodriguez, C. M.,Vina-Rodriguez, J.,Gonzalez-Diaz, A. Vitamin D and nutritional status are related to bone fractures in alcoholics. Alcohol Alcohol. 2011. 46:148–55 https://www.ncbi.nlm.nih.gov/pubmed/21248027 21248027 | X | X
195. | Goodpaster, B. H.,Katsiaras, A.,Kelley, D. E. Enhanced fat oxidation through physical activity is associated with improvements in insulin sensitivity in obesity. Diabetes. 2003. 52:2191–7 https://www.ncbi.nlm.nih.gov/pubmed/12941756 12941756 | | X
196. | Gopinath, B.,Flood, V. M.,Burlutksy, G.,Liew, G.,Mitchell, P. Carbohydrate nutrition variables and risk of disability in instrumental activities of daily living. Eur J Nutr. 2018. #volume#:#pages# https://www.ncbi.nlm.nih.gov/pubmed/30448879 | | | | X
197. | Gopinath, B.,Russell, J.,Flood, V. M.,Burlutsky, G.,Mitchell, P. Adherence to dietary guidelines positively affects quality of life and functional status of older adults. J Acad Nutr Diet. 2014. 114:220–9 https://www.ncbi.nlm.nih.gov/pubmed/24239401 24239401 | | | | X
198. | Gordon, M. M.,Bopp, M. J.,Easter, L.,Miller, G. D.,Lyles, M. F.,Houston, D. K., Nicklas, B. J.,Kritchevsky, S. B. Effects of dietary protein on the composition of weight loss in post-menopausal women. J Nutr Health Aging. 2008. 12:505–9 https://www.ncbi.nlm.nih.gov/pubmed/18810296 18810296 | | | | X
199. | Gorgey, A. S.,Dolbow, D. R.,Cifu, D. X.,Gater, D. R. Neuromuscular electrical stimulation attenuates thigh skeletal muscles atrophy but Xt trunk muscles after spinal cord injury. J Electromyogr Kinesiol. 2013. 23:977–84 https://www.ncbi.nlm.nih.gov/pubmed/23683374 23683374 | X | | | | | | | X
200. | Gorissen, S. H.,Horstman, A. M.,Franssen, R.,Kouw, I. W.,Wall, B. T.,Burd, N. A., de Groot, L. C.,van Loon, L. J. Habituation to low or high protein intake does not modulate basal or postprandial muscle protein synthesis rates: a randomized trial. Am J Clin Nutr. 2017. 105:332–342 https://www.ncbi.nlm.nih.gov/pubmed/27903518 27903518 | | | | X
201. | Grabovac, I.,Haider, S.,Winzer, E.,Kapan, A.,Schindler, K. E.,Lackinger, C.,Dorner, T. E. Changes in health parameters in older lay volunteers who delivered a lifestyle-based program to frail older people at home. Wien Klin Wochenschr. 2018. 130:637–644 https://www.ncbi.nlm.nih.gov/pubmed/30094663 30094663 | | X | | X
202. | Graciani, A.,Garcia-Esquinas, E.,Lopez-Garcia, E.,Banegas, J. R.,Rodriguez-Artalejo, F. Ideal Cardiovascular Health and Risk of Frailty in Older Adults. Circ Cardiovasc Qual Outcomes. 2016. 9:239–45 https://www.ncbi.nlm.nih.gov/pubmed/27166207 27166207 | | | | X
203. | Granic, A.,Jagger, C.,Davies, K.,Adamson, A.,Kirkwood, T.,Hill, T. R.,Siervo, M., Mathers, J. C.,Sayer, A. A. Effect of Dietary Patterns on Muscle Strength and Physical Performance in the Very Old: Findings from the Newcastle 85+ Study. PLoS One. 2016. 11:e0149699 https://www.ncbi.nlm.nih.gov/pubmed/26934360 26934360 | | | | X
204. | Granic, A.,Mendonça, N.,Sayer, A. A.,Hill, T. R.,Davies, K.,Adamson, A.,Siervo, M., Mathers, J. C.,Jagger, C. Low protein intake, muscle strength and physical performance in the very old: The Newcastle 85+ Study. Clinical Nutrition. 2018. 37:2260–2270 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L619465343 10.1016/j.clnu.2017.11.005 29191494 | | X
205. | Gray-Donald, K.,St-Arnaud-McKenzie, D.,Gaudreau, P.,Morais, J. A.,Shatenstein, B.,Payette, H. Protein intake protects against weight loss in healthy community-dwelling older adults. J Nutr. 2014. 144:321–6 https://www.ncbi.nlm.nih.gov/pubmed/24357473 24357473 | X | | | X
206. | Green, M. W.,Elliman, N. A.,Kretsch, M. J. Weight loss strategies, stress, and cognitive function: supervised versus unsupervised dieting. Psychoneuroendocrinology. 2005. 30:908–18 https://www.ncbi.nlm.nih.gov/pubmed/15970392 15970392 | | X | | X
207. | Guligowska, A.,Piglowska, M.,Fife, E.,Kostka, J.,Soltysik, B. K.,Kroc, L.,Kostka, T. Inappropriate nutrients intake is associated with lower functional status and inferior quality of life in older adults with depression. Clin Interv Aging. 2016. 11:1505–1517 https://www.ncbi.nlm.nih.gov/pubmed/27822023 27822023 | X | X | | X
208. | Hagan, K. A.,Chiuve, S. E.,Stampfer, M. J.,Katz, J. N.,Grodstein, F. Greater Adherence to the Alternative Healthy Eating Index Is Associated with Lower Incidence of Physical Function Impairment in the Nurses’ Health Study. J Nutr. 2016. 146:1341–7 https://www.ncbi.nlm.nih.gov/pubmed/27170727 27170727 | | | | X
209. | Hagan, K. A.,Grodstein, F. The Alternative Healthy Eating Index and Physical Function Impairment in Men. J Nutr Health Aging. 2019. 23:459–465 https://www.ncbi.nlm.nih.gov/pubmed/31021363 31021363 | | | | X
210. | Hai, S.,Wang, H.,Cao, L.,Liu, P.,Zhou, J.,Yang, Y.,Dong, B. Association between sarcopenia with lifestyle and family function among community-dwelling Chinese aged 60 years and older. BMC Geriatr. 2017. 17:187 https://www.ncbi.nlm.nih.gov/pubmed/28821239 28821239 | X
211. | Halliday, T. M.,Savla, J.,Marinik, E. L.,Hedrick, V. E.,Winett, R. A.,Davy, B. M. Resistance training is associated with spontaneous changes in aerobic physical activity but not overall diet quality in adults with prediabetes. Physiol Behav. 2017. 177:49–56 https://www.ncbi.nlm.nih.gov/pubmed/28414072 28414072 | | | | X
212. | Han, P.,Zhao, J.,Guo, Q.,Wang, J.,Zhang, W.,Shen, S.,Wang, X.,Dong, R.,Ma, Y., Kang, L.,Fu, L.,Jia, L.,Han, X.,He, Z.,Bao, Y.,Wang, L.,Niu, K. Incidence, risk factors, and the protective effect of high body mass index against sarcopenia in suburb-dwelling elderly Chinese populations. Journal of Nutrition, Health and Aging. 2016. 20:1056–1060 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L608644619 10.1007/s12603-016-0704-3 | | X
213. | Haub, M. D.,Wells, A. M.,Campbell, W. W. Beef and soy-based food supplements differentially affect serum lipoprotein-lipid profiles because of changes in carbohydrate intake and novel nutrient intake ratios in older men who resistive-train. Metabolism. 2005. 54:769–74 https://www.ncbi.nlm.nih.gov/pubmed/15931612 15931612 | | X | X
214. | Haub, M. D.,Wells, A. M.,Tarnopolsky, M. A.,Campbell, W. W. Effect of protein source on resistive-training-induced changes in body composition and muscle size in older men. Am J Clin Nutr. 2002. 76:511–7 https://www.ncbi.nlm.nih.gov/pubmed/12197993 12197993 | | X
215. | Hayashi, F.,Matsumoto, Y.,Momoki, C.,Yuikawa, M.,Okada, G.,Hamakawa, E., Kawamura, E.,Hagihara, A.,Toyama, M.,Fujii, H.,Kobayashi, S.,Iwai, S.,Morikawa, H.,Enomoto, M.,Tamori, A.,Kawada, N.,Habu, D. Physical inactivity and insufficient dietary intake are associated with the frequency of sarcopenia in patients with compensated viral liver cirrhosis. Hepatol Res. 2013. 43:1264–75 https://www.ncbi.nlm.nih.gov/pubmed/23489325 23489325 | | | | | | | | X
216. | Hayashi, F.,Momoki, C.,Yuikawa, M.,Simotani, Y.,Kawamura, E.,Hagihara, A.,Fujii, H.,Kobayashi, S.,Iwai, S.,Morikawa, H.,EXmoto, M.,Tamori, A.,Kawada, N.,Ohfuji, S.,Fukusima, W.,Habu, D. Nutritional status in relation to lifestyle in patients with compensated viral cirrhosis. World J Gastroenterol. 2012. 18:5759–70 https://www.ncbi.nlm.nih.gov/pubmed/23155318 23155318 | | X | | X
217. | Hazreen, M. A.,Su, T. T.,Jalaludin, M. Y.,Dahlui, M.,Chinna, K.,Ismail, M.,Murray, L.,Cantwell, M.,Al Sadat, N. An exploratory study on risk factors for chronic non-communicable diseases among adolescents in Malaysia: overview of the Malaysian Health and Adolescents Longitudinal Research Team study (The MyHeART study). BMC Public Health. 2014. 14 Suppl 3:S6 https://www.ncbi.nlm.nih.gov/pubmed/25437068 | X | X
218. | Hegerova, P.,Dedkova, Z.,Sobotka, L. Early nutritional support and physiotherapy improved long-term self-sufficiency in acutely ill older patients. Nutrition. 2015. 31:166–70 https://www.ncbi.nlm.nih.gov/pubmed/25466662 25466662 | | | | | | | | X
219. | Helms, E. R.,Zinn, C.,Rowlands, D. S.,Naidoo, R.,Cronin, J. High-protein, low-fat, short-term diet results in less stress and fatigue than moderate-protein moderate-fat diet during weight loss in male weightlifters: a pilot study. Int J Sport Nutr Exerc Metab. 2015. 25:163–70 https://www.ncbi.nlm.nih.gov/pubmed/25028958 25028958 | | | | | | | | X
220. | Hermanussen, H. H.,Menendez, M. E.,Chen, N. C.,Ring, D.,Vranceanu, A. M. Predictors of Upper-Extremity Physical Function in Older Adults. Arch Bone Jt Surg. 2016. 4:359–365 https://www.ncbi.nlm.nih.gov/pubmed/27847850 27847850 | X
221. | Herrema, A. L.,Westerman, M. J.,van Dongen, E. J. I.,Kudla, U.,Veltkamp, M. Combined Protein-Rich Diet With Resistance Exercise Intervention to Counteract Sarcopenia: A Qualitative Study on Drivers and Barriers of Compliance. J Aging Phys Act. 2018. 26:106–113 https://www.ncbi.nlm.nih.gov/pubmed/28595022 28595022 | X | X | | X
222. | Hietavala, E. M.,Puurtinen, R.,Kainulainen, H.,Mero, A. A. Low-protein vegetarian diet does not have a short-term effect on blood acid-base status but raises oxygen consumption during submaximal cycling. J Int Soc Sports Nutr. 2012. 9:50 https://www.ncbi.nlm.nih.gov/pubmed/23181739 23181739 | | X | | X
223. | Hirsch, K. R.,Tweedell, A. J.,Kleinberg, C. R.,Gerstner, G. R.,Barnette, T. J.,Mota, J. A.,Smith-Ryan, A. E.,Ryan, E. D. The Influence of Habitual Protein Intake on Body Composition and Muscular Strength in Career Firefighters. J Am Coll Nutr. 2018. 37:620–626 https://www.ncbi.nlm.nih.gov/pubmed/29702029 29702029 | X
224. | Ho, R. C.,Davy, K. P.,Hickey, M. S.,Summers, S. A.,Melby, C. L. Behavioral, metabolic, and molecular correlates of lower insulin sensitivity in Mexican-Americans. Am J Physiol Endocrinol Metab. 2002. 283:E799–808 https://www.ncbi.nlm.nih.gov/pubmed/12217898 12217898 | X | X | | X
225. | Hodge, A. M.,O’Dea, K.,English, D. R.,Giles, G. G.,Flicker, L. Dietary patterns as predictors of successful ageing. J Nutr Health Aging. 2014. 18:221–7 https://www.ncbi.nlm.nih.gov/pubmed/24626747 24626747 | | | | X
226. | Holm, L.,Nordsborg, N. B. Supplementing a normal diet with protein yields a moderate improvement in the robust gains in muscle mass and strength induced by resistance training in older individuals. Am J Clin Nutr. 2017. 106:971–972 https://www.ncbi.nlm.nih.gov/pubmed/28877892 28877892 | | | | | X
227. | Holwerda, A. M.,Kouw, I. W.,Trommelen, J.,Halson, S. L.,Wodzig, W. K.,Verdijk, L. B.,van Loon, L. J. Physical Activity Performed in the Evening Increases the Overnight Muscle Protein Synthetic Response to Presleep Protein Ingestion in Older Men. J Nutr. 2016. 146:1307–14 https://www.ncbi.nlm.nih.gov/pubmed/27281811 27281811 | | X
228. | Hopkins, M.,Finlayson, G.,Duarte, C.,Whybrow, S.,Ritz, P.,Horgan, G. W.,Blundell, J. E.,Stubbs, R. J. Modelling the associations between fat-free mass, resting metabolic rate and energy intake in the context of total energy balance. Int J Obes (Lond). 2016. 40:312–8 https://www.ncbi.nlm.nih.gov/pubmed/26278004 26278004 | | X | | X
229. | Houston, D. K.,Nicklas, B. J.,Ding, J.,Harris, T. B.,Tylavsky, F. A.,Newman, A. B., Lee, J. S.,Sahyoun, N. R.,Visser, M.,Kritchevsky, S. B. Dietary protein intake is associated with lean mass change in older, community-dwelling adults: the Health, Aging, and Body Composition (Health ABC) Study. Am J Clin Nutr. 2008. 87:150–5 https://www.ncbi.nlm.nih.gov/pubmed/18175749 18175749 | | X | X
230. | Houston, D. K.,Stevens, J.,Cai, J.,Haines, P. S. Dairy, fruit, and vegetable intakes and functional limitations and disability in a biracial cohort: the Atherosclerosis Risk in Communities Study. Am J Clin Nutr. 2005. 81:515–22 https://www.ncbi.nlm.nih.gov/pubmed/15699243 15699243 | | X
231. | Houston, D. K.,Tooze, J. A.,Garcia, K.,Visser, M.,Rubin, S.,Harris, T. B.,Newman, A. B.,Kritchevsky, S. B. Protein Intake and Mobility Limitation in Community-Dwelling Older Adults: the Health ABC Study. J Am Geriatr Soc. 2017. 65:1705–1711 https://www.ncbi.nlm.nih.gov/pubmed/28306154 28306154 | | | | X
232. | Hruby, A.,Sahni, S.,Bolster, D.,Jacques, P. F. Protein Intake and Functional Integrity in Aging: The Framingham Heart Study Offspring. J Gerontol A Biol Sci Med Sci. 2018. #volume#:#pages# https://www.ncbi.nlm.nih.gov/pubmed/30247514 | | X | | X
233. | Hu, S.,Gu, Y.,Lu, Z.,Zhang, Q.,Liu, L.,Meng, G.,Yao, Z.,Wu, H.,Bao, X.,Chi, V. T. Q.,Zhang, S.,Liu, M.,Wang, Y.,Wang, L.,Zheng, L.,Wang, X.,Tian, C.,Fu, J.,Sun, S., Zhou, M.,Jia, Q.,Song, K.,Sun, Z.,Niu, K. Relationship Between Grip Strength and Prediabetes in a Large-Scale Adult Population. Am J Prev Med. 2019. 56:844–851 https://www.ncbi.nlm.nih.gov/pubmed/31003803 31003803 | X | X | | X
234. | Hu, T. Y.,Chen, Y. C.,Lin, P.,Shih, C. K.,Bai, C. H.,Yuan, K. C.,Lee, S. Y.,Chang, J. S. Testosterone-Associated Dietary Pattern Predicts Low Testosterone Levels and Hypogonadism. Nutrients. 2018. 10:#pages# https://www.ncbi.nlm.nih.gov/pubmed/30453566 | X
235. | Huang, Y. C.,Wahlqvist, M. L.,Lo, Y. T. C.,Lin, C.,Chang, H. Y.,Lee, M. S. A non-invasive modifiable Healthy Ageing Nutrition Index (HANI) predicts longevity in free-living older Taiwanese. Scientific reports. 2018. 8:7113 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L629354978 10.1038/s41598-018-24625-3 29739965 | | X | | | | | X
236. | Hughes, S. L.,Tussing-Humphreys, L.,Schiffer, L.,Smith-Ray, R.,Marquez, D. X., DeMott, A. D.,Berbaum, M. L.,Fitzgibbon, M. L. Fit & Strong! Plus Trial Outcomes for Obese Older Adults with Osteoarthritis. Gerontologist. 2018. #volume#:#pages# https://www.ncbi.nlm.nih.gov/pubmed/30476065 | | X | | X
237. | Hutasuhut, F.,Ryoto, V. Associations between muscle grip strength with age, body mass index, waist-to-hip ratio, level of independent, physical activity level and macronutrient intake in elderly women. Pakistan Journal of Nutrition. 2014. 13:409–414 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L600386359 10.3923/pjn.2014.409.414 | X | | | | | | X
238. | Hutchins-Wiese, H. L.,Kleppinger, A.,Annis, K.,Liva, E.,Lammi-Keefe, C. J., Durham, H. A.,Kenny, A. M. The impact of supplemental n-3 long chain polyunsaturated fatty acids and dietary antioxidants on physical performance in postmenopausal women. J Nutr Health Aging. 2013. 17:76–80 https://www.ncbi.nlm.nih.gov/pubmed/23299384 23299384 | | X
239. | Huuskonen, J.,Vaisanen, S. B.,Kroger, H.,Jurvelin, C.,Bouchard, C.,Alhava, E., Rauramaa, R. Determinants of bone mineral density in middle aged men: a population-based study. Osteoporos Int. 2000. 11:702–8 https://www.ncbi.nlm.nih.gov/pubmed/11095174 11095174 | X | X
240. | Iglay, H. B.,Apolzan, J. W.,Gerrard, D. E.,Eash, J. K.,Anderson, J. C.,Campbell, W. W. Moderately increased protein intake predominately from egg sources does not influence whole body, regional, or muscle composition responses to resistance training in older people. J Nutr Health Aging. 2009. 13:108–14 https://www.ncbi.nlm.nih.gov/pubmed/19214338 19214338 | | X | X
241. | Irazusta, A.,Gil, S.,Ruiz, F.,Gondra, J.,Jauregi, A.,Irazusta, J.,Gil, J. Exercise, physical fitness, and dietary habits of first-year female nursing students. Biol Res Nurs. 2006. 7:175–86 https://www.ncbi.nlm.nih.gov/pubmed/16552945 16552945 | X | X | | X
242. | Isanejad, M.,Mursu, J.,Sirola, J.,Kroger, H.,Rikkonen, T.,Tuppurainen, M.,Erkkila, A. T. Dietary protein intake is associated with better physical function and muscle strength among elderly women. Br J Nutr. 2016. 115:1281–91 https://www.ncbi.nlm.nih.gov/pubmed/26857389 26857389 | | X
243. | Isanejad, M.,Mursu, J.,Sirola, J.,Kroger, H.,Rikkonen, T.,Tuppurainen, M.,Erkkila, A. T. Association of protein intake with the change of lean mass among elderly women: The Osteoporosis Risk Factor and Prevention - Fracture Prevention Study (OSTPRE-FPS). J Nutr Sci. 2015. 4:e41 https://www.ncbi.nlm.nih.gov/pubmed/26793306 26793306 | | X
244. | Izumotani, K.,Hagiwara, S.,Izumotani, T.,Miki, T.,Morii, H.,Nishizawa, Y. Risk factors for osteoporosis in men. J Bone Miner Metab. 2003. 21:86–90 https://www.ncbi.nlm.nih.gov/pubmed/12601572 12601572 | | X
245. | Jacob, M. E.,Yee, L. M.,Diehr, P. H.,Arnold, A. M.,Thielke, S. M.,Chaves, P. H., Gobbo, L. D.,Hirsch, C.,Siscovick, D.,Newman, A. B. Can a Healthy Lifestyle Compress the Disabled Period in Older Adults?. J Am Geriatr Soc. 2016. 64:1952–1961 https://www.ncbi.nlm.nih.gov/pubmed/27603679 27603679 | | | | X
246. | Jadczak, A. D.,Luscombe-Marsh, N.,Taylor, P.,Barnard, R.,Makwana, N.,Visvanathan, R. The EXPRESS Study: exercise and Protein Effectiveness Supplementation Study supporting autonomy in community dwelling frail older people study protocol for a randomized controlled pilot and feasibility study. Pilot and feasibility studies. 2018. 4:#pages# https://www.cochranelibrary.com/central/doi/10.1002/central/CN-01755477/full | X | X
247. | Jarvis, M.,McNaughton, L.,Seddon, A.,Thompson, D. The acute 1-week effects of the Zone diet on body composition, blood lipid levels, and performance in recreational endurance athletes. J Strength Cond Res. 2002. 16:50–7 https://www.ncbi.nlm.nih.gov/pubmed/11834107 11834107 | | | | | | | | X
248. | Jenkinson, C. M.,Doherty, M.,Avery, A. J.,Read, A.,Taylor, M. A.,Sach, T. H., Silcocks, P.,Muir, K. R. Effects of dietary intervention and quadriceps strengthening exercises on pain and function in overweight people with knee pain: randomised controlled trial. BMJ (clinical research ed.). 2009. 339:b3170 https://www.cochranelibrary.com/central/doi/10.1002/central/CN-00719642/full | | X | | X
249. | Jensen, G. L.,Roy, M. A.,Buchanan, A. E.,Berg, M. B. Weight loss intervention for obese older women: improvements in performance and function. Obes Res. 2004. 12:1814–20 https://www.ncbi.nlm.nih.gov/pubmed/15601977 15601977 | | X
250. | Jeong, G. W.,Kim, Y. J.,Park, S.,Kim, H.,Kwon, O. Associations of recommended food score and physical performance in Korean elderly. BMC Public Health. 2019. 19:128 https://www.ncbi.nlm.nih.gov/pubmed/30700281 30700281 | X
251. | Jin, Y.,Tanaka, T.,Ma, Y.,Bandinelli, S.,Ferrucci, L.,Talegawkar, S. A. Cardiovascular Health Is Associated With Physical Function Among Older Community Dwelling Men and Women. J Gerontol A Biol Sci Med Sci. 2017. 72:1710–1716 https://www.ncbi.nlm.nih.gov/pubmed/28184412 28184412 | | X
252. | Jo, E.,Worts, P. R.,Elam, M. L.,Brown, A. F.,Khamoui, A. V.,Kim, D. H.,Yeh, M. C., Ormsbee, M. J.,Prado, C. M.,Cain, A.,Snyder, K.,Kim, J. S. Resistance training during a 12-week protein supplemented VLCD treatment enhances weight-loss outcomes in obese patients. Clin Nutr. 2019. 38:372–382 https://www.ncbi.nlm.nih.gov/pubmed/29352654 29352654 | | X
253. | Johnson, C. S.,Mahon, A.,McLeod, W. Nutritional, functional and psychosocial correlates of disability among older adults. J Nutr Health Aging. 2006. 10:45–50 https://www.ncbi.nlm.nih.gov/pubmed/16453057 16453057 | X
254. | Johnson, L. J.,McCool, A. C. Dietary intake and nutritional status of older adult homeless women: a pilot study. J Nutr Elder. 2003. 23:1–21 https://www.ncbi.nlm.nih.gov/pubmed/14650550 | X | X
255. | Josse, A. R.,Atkinson, S. A.,Tarnopolsky, M. A.,Phillips, S. M. Increased consumption of dairy foods and protein during diet- and exercise-induced weight loss promotes fat mass loss and lean mass gain in overweight and obese premenopausal women. J Nutr. 2011. 141:1626–34 https://www.ncbi.nlm.nih.gov/pubmed/21775530 21775530 | | X | X
256. | Josse, A. R.,Atkinson, S. A.,Tarnopolsky, M. A.,Phillips, S. M. Consumption of higher dairy and dietary protein during diet- and exercise-induced weight loss promotes a metabolically favourable body composition change in overweight and obese young women. FASEB journal. 2011. 25:#pages# https://www.cochranelibrary.com/central/doi/10.1002/central/CN-01033363/full | X
257. | Joy, J. M.,Lowery, R. P.,Wilson, J. M.,Purpura, M.,De Souza, E. O.,Wilson, S. M., Kalman, D. S.,Dudeck, J. E.,Jager, R. The effects of 8 weeks of whey or rice protein supplementation on body composition and exercise performance. Nutr J. 2013. 12:86 https://www.ncbi.nlm.nih.gov/pubmed/23782948 23782948 | | X
258. | Jprn, Umin A cross-over trial for preventing frailty in the community dwelling older adults. Http://www.who.int/trialsearch/trial2.aspx? Trialid=jprn-umin000011435. 2013. #volume#:#pages# https://www.cochranelibrary.com/central/doi/10.1002/central/CN-01796456/full | X | | | | X
259. | Jprn, Umin A community-based intervention using TAKE10! program to improve dietary habit and to promote physical activity among the elderly: a cluster randomizes trail. Http://www.who.int/trialsearch/trial2.aspx? Trialid=jprn-umin000007357. 2012. #volume#:#pages# https://www.cochranelibrary.com/central/doi/10.1002/central/CN-01830944/full | X | | | | X
260. | Jung, M.,Park, S.,Kim, H.,Kwon, O. Association of Diet Quality with Low Muscle Mass-Function in Korean Elderly. Int J Environ Res Public Health. 2019. 16:#pages# https://www.ncbi.nlm.nih.gov/pubmed/31370245 | X
261. | Jyväkorpi, S. K.,Urtamo, A.,Pitkälä, K. H.,Strandberg, T. E. Nutrition, daily walking and resilience are associated with physical function in the oldest old men. Journal of Nutrition, Health and Aging. 2018. 22:1176–1182 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L626914180 10.1007/s12603-018-1136-z | X
262. | Kang, H. J.,Jun, D. W.,Lee, S. M.,Jang, E. C.,Cho, Y. K. Low salt and low calorie diet does not reduce more body fat than same calorie diet: a randomized controlled study. Oncotarget. 2018. 9:8521–8530 https://www.ncbi.nlm.nih.gov/pubmed/29492213 29492213 | | X
263. | Karelis, A. D.,Lavoie, M. E.,Fontaine, J.,Messier, V.,Strychar, I.,Rabasa-Lhoret, R., Doucet, E. Anthropometric, metabolic, dietary and psychosocial profiles of underreporters of energy intake: a doubly labeled water study among overweight/obese postmenopausal women--a Montreal Ottawa New Emerging Team study. Eur J Clin Nutr. 2010. 64:68–74 https://www.ncbi.nlm.nih.gov/pubmed/19756035 19756035 | X
264. | Karelis, A. D.,Messier, V.,Suppere, C.,Briand, P.,Rabasa-Lhoret, R. Effect of cysteine-rich whey protein (immunocal(R)) supplementation in combination with resistance training on muscle strength and lean body mass in non-frail elderly subjects: a randomized, double-blind controlled study. J Nutr Health Aging. 2015. 19:531–6 https://www.ncbi.nlm.nih.gov/pubmed/25923482 25923482 | | X
265. | Keller, H. H. Reliance on others for food-related activities of daily living. J Nutr Elder. 2005. 25:43–59 https://www.ncbi.nlm.nih.gov/pubmed/16891262 16891262 | X | X
266. | Kemmler, W.,Teschler, M.,Weissenfels, A.,Bebenek, M.,von Stengel, S.,Kohl, M., Freiberger, E.,Goisser, S.,Jakob, F.,Sieber, C.,Engelke, K. Whole-body electromyostimulation to fight sarcopenic obesity in community-dwelling older women at risk. Resultsof the randomized controlled FORMOsA-sarcopenic obesity study. Osteoporosis International. 2016. 27:3261–3270 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L612665826 10.1007/s00198-016-3662-z 27289534 | | X
267. | Kephart, W. C.,Pledge, C. D.,Roberson, P. A.,Mumford, P. W.,Romero, M. A., Mobley, C. B.,Martin, J. S.,Young, K. C.,Lowery, R. P.,Wilson, J. M.,Huggins, K. W.,Roberts, M. D. The Three-Month Effects of a Ketogenic Diet on Body Composition, Blood Parameters, and Performance Metrics in CrossFit Trainees: A Pilot Study. Sports (Basel). 2018. 6:#pages# https://www.ncbi.nlm.nih.gov/pubmed/29910305 | | X | | | | | | X
268. | Kido, Y. The Issue of Nutrition in an Aging Society. J Nutr Sci Vitaminol (Tokyo). 2015. 61 Suppl:S176–7 https://www.ncbi.nlm.nih.gov/pubmed/26598846 26598846 | X
269. | Kim, I. Y.,Schutzler, S.,Schrader, A. M.,Spencer, H. J.,Azhar, G.,Wolfe, R. R., Ferrando, A. A. Protein intake distribution pattern does not affect anabolic response, lean body mass, muscle strength or function over 8 weeks in older adults: A randomized-controlled trial. Clin Nutr. 2018. 37:488–493 https://www.ncbi.nlm.nih.gov/pubmed/28318687 28318687 | | X
270. | Kim, I. Y.,Schutzler, S.,Schrader, A.,Spencer, H.,Kortebein, P.,Deutz, N. E.,Wolfe, R. R.,Ferrando, A. A. Quantity of dietary protein intake, but not pattern of intake, affects net protein balance primarily through differences in protein synthesis in older adults. Am J Physiol Endocrinol Metab. 2015. 308:E21–8 https://www.ncbi.nlm.nih.gov/pubmed/25352437 25352437 | | X | | X
271. | Kim, J.,Jung, M.,Hong, Y. P.,Park, J. D.,Choi, B. S. Physical activity in adolescence has a positive effect on bone mineral density in young men. J Prev Med Public Health. 2013. 46:89–95 https://www.ncbi.nlm.nih.gov/pubmed/23573373 23573373 | X | X | | X
272. | Kimokoti, R. W.,Newby, P. K.,Gona, P.,Zhu, L.,Jasuja, G. K.,Pencina, M. J.,McKeon-O’Malley, C.,Fox, C. S.,D’Agostino, R. B.,Millen, B. E. Diet quality, physical activity, smoking status, and weight fluctuation are associated with weight change in women and men. J Nutr. 2010. 140:1287–93 https://www.ncbi.nlm.nih.gov/pubmed/20484553 20484553 | | | | X
273. | Kirk, B.,Mooney, K.,Amirabdollahian, F.,Khaiyat, O. Exercise and Dietary-Protein as a Countermeasure to Skeletal Muscle Weakness: Liverpool Hope University - Sarcopenia Aging Trial (LHU-SAT). Front Physiol. 2019. 10:445 https://www.ncbi.nlm.nih.gov/pubmed/31133863 31133863 | | X | | X
274. | Kirwan, R. D.,Kordick, L. K.,McFarland, S.,Lancaster, D.,Clark, K.,Miles, M. P. Dietary, anthropometric, blood-lipid, and performance patterns of American College Football Players during 8 weeks of training. Int J Sport Nutr Exerc Metab. 2012. 22:444–51 https://www.ncbi.nlm.nih.gov/pubmed/22805315 22805315 | | | | | | | | X
275. | Kochlik, B.,Gerbracht, C.,Grune, T.,Weber, D. The Influence of Dietary Habits and Meat Consumption on Plasma 3-Methylhistidine-A Potential Marker for Muscle Protein Turnover. Mol Nutr Food Res. 2018. 62:e1701062 https://www.ncbi.nlm.nih.gov/pubmed/29573154 29573154 | X | X | | X
276. | Kojima, N.,Kim, M.,Saito, K.,Yoshida, H.,Yoshida, Y.,Hirano, H.,Obuchi, S.,Shimada, H.,Suzuki, T.,Kim, H. Lifestyle-Related Factors Contributing to Decline in Knee Extension Strength among Elderly Women: A Cross-Sectional and Longitudinal Cohort Study. PLoS One. 2015. 10:e0132523 https://www.ncbi.nlm.nih.gov/pubmed/26177292 26177292 | | | | X
277. | Kolarzyk, E.,Ostachowska-Gasior, A.,Skop, A. The protein participation in daily diet and nutritional status of medical students in Krakow. Rocz Akad Med Bialymst. 2005. 50 Suppl 1:39–41 https://www.ncbi.nlm.nih.gov/pubmed/16119623 16119623 | X | X
278. | Komatsu, F.,Kagawa, Y.,Kawabata, T.,Kaneko, Y.,Ishiguro, K. Relationship of dietary habits and obesity to oxidative stress in Palauan people: compared with Japanese and Mongolian people. Curr Aging Sci. 2009. 2:214–22 https://www.ncbi.nlm.nih.gov/pubmed/20021416 20021416 | | | | | | | X
279. | Komatsu, F.,Kagawa, Y.,Kawabata, T.,Kaneko, Y.,Purvee, B.,Otgon, J., Chimedregzen, U. Dietary habits of Mongolian people, and their influence on lifestyle-related diseases and early aging. Curr Aging Sci. 2008. 1:84–100 https://www.ncbi.nlm.nih.gov/pubmed/20021377 20021377 | X | X | | | | | X
280. | Komatsu, F.,Kagawa, Y.,Sakuma, M.,Kawabata, T.,Kaneko, Y.,Otgontuya, D., Chimedregzen, U.,Narantuya, L.,Purvee, B. Investigation of oxidative stress and dietary habits in Mongolian people, compared to Japanese people. Nutr Metab (Lond). 2006. 3:21 https://www.ncbi.nlm.nih.gov/pubmed/16759377 16759377 | X | X
281. | Koopman, R. Dietary protein and exercise training in ageing. Proc Nutr Soc. 2011. 70:104–13 https://www.ncbi.nlm.nih.gov/pubmed/21092364 21092364 | X
282. | Koppes, L. L.,Boon, N.,Nooyens, A. C.,van Mechelen, W.,Saris, W. H. Macronutrient distribution over a period of 23 years in relation to energy intake and body fatness. Br J Nutr. 2009. 101:108–15 https://www.ncbi.nlm.nih.gov/pubmed/18466652 18466652 | | | | X
283. | Koster, A.,Penninx, B. W. J. H.,Newman, A. B.,Visser, M.,Van Gool, C. H.,Harris, T. B.,Van Eijk, J. Th M.,Kempen, G. I. J. M.,Brach, J. S.,Simonsick, E. M.,Houston, D. K.,Tylavsky, F. A.,Rubin, S. M.,Kritchevsky, S. B. Lifestyle factors and incident mobility limitation in obese and non-obese older adults. Obesity. 2007. 15:3122–3132 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L351256676 18198323 | | | | X
284. | Kukuljan, S.,Nowson, C. A.,Sanders, K.,Daly, R. M. Effects of resistance exercise and fortified milk on skeletal muscle mass, muscle size, and functional performance in middle-aged and older men: an 18-mo randomized controlled trial. J Appl Physiol (1985). 2009. 107:1864–73 https://www.ncbi.nlm.nih.gov/pubmed/19850735 19850735 | | X
285. | Kuwabara, A.,Tsugawa, N.,Kondo, H.,Ao, M.,Fujiwara, H.,Hosokawa, N., Matsumoto, S.,Tanaka, K.,Nakano, T. Associations between serum 25-hydroxyvitamin D3 level and skeletal muscle mass and lower limb muscle strength in Japanese middle-aged subjects. Osteoporos Sarcopenia. 2017. 3:53–58 https://www.ncbi.nlm.nih.gov/pubmed/30775503 30775503 | | X
286. | Kwon, J.,Yoshida, Y.,Yoshida, H.,Kim, H.,Suzuki, T.,Lee, Y. Effects of a combined physical training and nutrition intervention on physical performance and health-related quality of life in prefrail older women living in the community: A randomized controlled trial. Journal of the American Medical Directors Association. 2015. 16:263.e1–263.e8 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L602005847 10.1016/j.jamda.2014.12.005 | | X
287. | Kynde, I.,Bjornsbo, K. S.,Tetens, I.,Heitmann, B. L. Dietary carbohydrates and change in physical performance of elderly Europeans: Survey in Europe on Nutrition and the Elderly, a Concerted Action (SENECA) 1993 and 1999. Public Health Nutr. 2010. 13:1186–90 https://www.ncbi.nlm.nih.gov/pubmed/19807934 19807934 | X | X
288. | Laclaustra, M.,Rodriguez-Artalejo, F.,Guallar-Castillon, P.,Banegas, J. R.,Graciani, A.,Garcia-Esquinas, E.,Lopez-Garcia, E. The inflammatory potential of diet is related to incident frailty and slow walking in older adults. Clin Nutr. 2019. #volume#:#pages# https://www.ncbi.nlm.nih.gov/pubmed/30737049 | | | | X
289. | LaFountain, R. A.,Miller, V. J.,Barnhart, E. C.,Hyde, P. N.,Crabtree, C. D., McSwiney, F. T.,Beeler, M. K.,Buga, A.,Sapper, T. N.,Short, J. A.,Bowling, M. L., Kraemer, W. J.,Simonetti, O. P.,Maresh, C. M.,Volek, J. S. Extended Ketogenic Diet and Physical Training Intervention in Military Personnel. Mil Med. 2019. #volume#:#pages# https://www.ncbi.nlm.nih.gov/pubmed/30877806 | | X | | | | | | X
290. | Lan, T. Y.,Hou, S. M.,Chen, C. Y.,Chang, W. C.,Lin, J.,Lin, C. C.,Liu, W. J.,Shih, T. F.,Tai, T. Y. Risk factors for hip fracture in older adults: a case-control study in Taiwan. Osteoporos Int. 2010. 21:773–84 https://www.ncbi.nlm.nih.gov/pubmed/19597907 19597907 | X | | | X
291. | Landi, F.,Calvani, R.,Tosato, M.,Martone, A. M.,Picca, A.,Ortolani, E.,Savera, G., Salini, S.,Ramaschi, M.,Bernabei, R.,Marzetti, E. Animal-Derived Protein Consumption Is Associated with Muscle Mass and Strength in Community-Dwellers: Results from the Milan EXPO Survey. J Nutr Health Aging. 2017. 21:1050–1056 https://www.ncbi.nlm.nih.gov/pubmed/29083447 29083447 | X | X
292. | Lauque, S.,Arnaud-Battandier, F.,Mansourian, R.,Guigoz, Y.,Paintin, M.,Nourhashemi, F.,Vellas, B. Protein-energy oral supplementation in malnourished nursing-home residents. A controlled trial. Age Ageing. 2000. 29:51–6 https://www.ncbi.nlm.nih.gov/pubmed/10690696 10690696 | | X | | | | | | X
293. | Lee, J. S.,Kritchevsky, S. B.,Tylavsky, F. A.,Harris, T.,Everhart, J.,Simonsick, E. M., Rubin, S. M.,Newman, A. B. Weight-loss intention in the well-functioning, community-dwelling elderly: associations with diet quality, physical activity, and weight change. Am J Clin Nutr. 2004. 80:466–74 https://www.ncbi.nlm.nih.gov/pubmed/15277172 15277172 | X | | | X
294. | Lee, K. S.,Lee, J. K.,Yeun, Y. R. Effects of a 10-Day Intensive Health Promotion Program Combining Diet and Physical Activity on Body Composition, Physical Fitness, and Blood Factors of Young Adults: A Randomized Pilot Study. Med Sci Monit. 2017. 23:1759–1767 https://www.ncbi.nlm.nih.gov/pubmed/28399076 28399076 | | X
295. | Leidy, H. J.,Carnell, N. S.,Mattes, R. D.,Campbell, W. W. Higher protein intake preserves lean mass and satiety with weight loss in pre-obese and obese women. Obesity (Silver Spring). 2007. 15:421–9 https://www.ncbi.nlm.nih.gov/pubmed/17299116 17299116 | | | | X
296. | Leite, M. L.,Nicolosi, A. Lifestyle correlates of anthropometric estimates of body adiposity in an Italian middle-aged and elderly population: a covariance analysis. Int J Obes (Lond). 2006. 30:926–34 https://www.ncbi.nlm.nih.gov/pubmed/16432539 16432539 | X
297. | Lemieux, F. C.,Filion, M. E.,Barbat-Artigas, S.,Karelis, A. D.,Aubertin-Leheudre, M. Relationship between different protein intake recommendations with muscle mass and muscle strength. Climacteric. 2014. 17:294–300 https://www.ncbi.nlm.nih.gov/pubmed/23931598 23931598 | X
298. | Leon-Munoz, L. M.,Garcia-Esquinas, E.,Lopez-Garcia, E.,Banegas, J. R.,Rodriguez-Artalejo, F. Major dietary patterns and risk of frailty in older adults: a prospective cohort study. BMC Med. 2015. 13:11 https://www.ncbi.nlm.nih.gov/pubmed/25601152 25601152 | | | | X
299. | Leon-Munoz, L. M.,Guallar-Castillon, P.,Lopez-Garcia, E.,Rodriguez-Artalejo, F. Mediterranean diet and risk of frailty in community-dwelling older adults. J Am Med Dir Assoc. 2014. 15:899–903 https://www.ncbi.nlm.nih.gov/pubmed/25127502 25127502 | | | | X
300. | Liberman, K.,Njemini, R.,Luiking, Y.,Forti, L. N.,Verlaan, S.,Bauer, J. M.,Memelink, R.,Brandt, K.,Donini, L. M.,Maggio, M.,Mets, T.,Wijers, S. L. J.,Sieber, C., Cederholm, T.,Bautmans, I. Thirteen weeks of supplementation of vitamin D and leucine-enriched whey protein nutritional supplement attenuates chronic low-grade inflammation in sarcopenic older adults: the PROVIDE study. Aging Clin Exp Res. 2019. 31:845–854 https://www.ncbi.nlm.nih.gov/pubmed/31049877 31049877 | | X | | | | | | X
301. | Lim, S. H.,Fan, S. H.,Say, Y. H. Plasma total antioxidant capacity (TAC) in obese Malaysian subjects. Malays J Nutr. 2012. 18:345–54 https://www.ncbi.nlm.nih.gov/pubmed/24568075 24568075 | X | X
302. | Lima-Silva, A. E.,Pires, F. O.,Bertuzzi, R.,Silva-Cavalcante, M. D.,Oliveira, R. S., Kiss, M. A.,Bishop, D. Effects of a low- or a high-carbohydrate diet on performance, energy system contribution, and metabolic responses during supramaximal exercise. Appl Physiol Nutr Metab. 2013. 38:928–34 https://www.ncbi.nlm.nih.gov/pubmed/23905657 23905657 | | | | X
303. | Lin, C. L.,Fang, T. C.,Gueng, M. K. Vascular dilatory functions of ovo-lactovegetarians compared with omnivores. Atherosclerosis. 2001. 158:247–51 https://www.ncbi.nlm.nih.gov/pubmed/11500198 11500198 | X | | | X
304. | Lindhardt, T.,Nielsen, M. H. Older patients’ use of technology for a post-discharge nutritional intervention – A mixed-methods feasibility study. International Journal of Medical Informatics. 2017. 97:312–321 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L613206355 10.1016/j.ijmedinf.2016.10.017 27919389 | | X | | | | | | X
305. | Lo, Y. C.,Wahlqvist, M. L.,Huang, Y. C.,Chuang, S. Y.,Wang, C. F.,Lee, M. S. Medical costs of a low skeletal muscle mass are modulated by dietary diversity and physical activity in community-dwelling older Taiwanese: a longitudinal study. Int J Behav Nutr Phys Act. 2017. 14:31 https://www.ncbi.nlm.nih.gov/pubmed/28288651 28288651 | X | X | | X
306. | Lockwood, C. M.,Moon, J. R.,Tobkin, S. E.,Walter, A. A.,Smith, A. E.,Dalbo, V. J., Cramer, J. T.,Stout, J. R. Minimal nutrition intervention with high-protein/low-carbohydrate and low-fat, nutrient-dense food supplement improves body composition and exercise benefits in overweight adults: A randomized controlled trial. Nutrition and Metabolism. 2008. 5:#pages# http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L351679532 10.1186/1743-7075-5-11 | | X
307. | Loenneke, J. P.,Balapur, A.,Thrower, A. D.,Syler, G.,Timlin, M.,Pujol, T. J. Short report: Relationship between quality protein, lean mass and bone health. Ann Nutr Metab. 2010. 57:219–20 https://www.ncbi.nlm.nih.gov/pubmed/21124023 21124023 | | | | X | X
308. | Loenneke, J. P.,Pujol, T. J. Sarcopenia: An emphasis on occlusion training and dietary protein. Hippokratia. 2011. 15:132–7 https://www.ncbi.nlm.nih.gov/pubmed/22110294 22110294 | X
309. | Longland, T. M.,Oikawa, S. Y.,Mitchell, C. J.,Devries, M. C.,Phillips, S. M. Higher compared with lower dietary protein during an energy deficit combined with intense exercise promotes greater lean mass gain and fat mass loss: a randomized trial. Am J Clin Nutr. 2016. 103:738–46 https://www.ncbi.nlm.nih.gov/pubmed/26817506 26817506 | | X | | | | | | X
310. | Lopez-Fontana, C. M.,Sanchez-Villegas, A.,Martinez-Gonzalez, M. A.,Martinez, J. A. Daily physical activity and macronutrient distribution of low-calorie diets jointly affect body fat reduction in obese women. Appl Physiol Nutr Metab. 2009. 34:595–602 https://www.ncbi.nlm.nih.gov/pubmed/19767793 19767793 | | | | X
311. | Loprinzi, P. D.,Frith, E. Effects of Sedentary Behavior, Physical Activity, Frequency of Protein Consumption, Lower Extremity Strength and Lean Mass on All-Cause Mortality. J Lifestyle Med. 2018. 8:8–15 https://www.ncbi.nlm.nih.gov/pubmed/29581955 29581955 | X
312. | Lord, C.,Chaput, J. P.,Aubertin-Leheudre, M.,Labonte, M.,Dionne, I. J. Dietary animal protein intake: association with muscle mass index in older women. J Nutr Health Aging. 2007. 11:383–7 https://www.ncbi.nlm.nih.gov/pubmed/17657359 17657359 | X | | | X
313. | Ma, W.,Hagan, K. A.,Heianza, Y.,Sun, Q.,Rimm, E. B.,Qi, L. Adult height, dietary patterns, and healthy aging. Am J Clin Nutr. 2017. 106:589–596 https://www.ncbi.nlm.nih.gov/pubmed/28592610 28592610 | | | | X
314. | Macchi, C.,Molino-Lova, R.,Polcaro, P.,Guarducci, L.,Lauretani, F.,Cecchi, F., Bandinelli, S.,Guralnik, J. M.,Ferrucci, L. Higher circulating levels of uric acid are prospectively associated with better muscle function in older persons. Mech Ageing Dev. 2008. 129:522–7 https://www.ncbi.nlm.nih.gov/pubmed/18534661 18534661 | X | X | | X
315. | Machado-Fragua, M. D.,Struijk, E. A.,Ballesteros, J. M.,Ortola, R.,Rodriguez-Artalejo, F.,Lopez-Garcia, E. Habitual coffee consumption and risk of falls in 2 European cohorts of older adults. Am J Clin Nutr. 2019. 109:1431–1438 https://www.ncbi.nlm.nih.gov/pubmed/31005970 31005970 | | X | | X
316. | Malafarina, V.,Serra Rexach, J. A.,Masanes, F.,Cruz-Jentoft, A. J. Effects of high-protein, high-calorie oral nutritional supplementation in malnourished older people in nursing homes: An observational, multi-center, prospective study (PROT-e-GER). Protocol and baseline population characteristics. Maturitas. 2019. 126:73–79 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L2002021384 10.1016/j.maturitas.2019.05.009 31239122 | X | X
317. | Malenfant, P.,Tremblay, A.,Doucet, E.,Imbeault, P.,Simoneau, J. A.,Joanisse, D. R. Elevated intramyocellular lipid concentration in obese subjects is not reduced after diet and exercise training. Am J Physiol Endocrinol Metab. 2001. 280:E632–9 https://www.ncbi.nlm.nih.gov/pubmed/11254471 11254471 | X | | | X
318. | Mamerow, M. M.,Mettler, J. A.,English, K. L.,Casperson, S. L.,Arentson-Lantz, E., Sheffield-Moore, M.,Layman, D. K.,Paddon-Jones, D. Dietary protein distribution positively influences 24-h muscle protein synthesis in healthy adults. J Nutr. 2014. 144:876–80 https://www.ncbi.nlm.nih.gov/pubmed/24477298 24477298 | | X | | X
319. | Mangano, K. M.,Sahni, S.,Kiel, D. P.,Tucker, K. L.,Dufour, A. B.,Hannan, M. T. Dietary protein is associated with musculoskeletal health independently of dietary pattern: the Framingham Third Generation Study. Am J Clin Nutr. 2017. 105:714–722 https://www.ncbi.nlm.nih.gov/pubmed/28179224 28179224 | | | | X
320. | Manios, Y.,Moschonis, G.,Koutsikas, K.,Papoutsou, S.,Petraki, I.,Bellou, E., Naoumi, A.,Kostea, S.,Tanagra, S. Changes in body composition following a dietary and lifestyle intervention trial: the postmenopausal health study. Maturitas. 2009. 62:58–65 https://www.ncbi.nlm.nih.gov/pubmed/19118956 19118956 | | X
321. | Manjunath, H.,Prabha, V.,Venkatesh, D.,Taklikar, R. H. Electromyogram, hand grip strength and time to fatigue in matched samples of vegetarians and nonvegetarians. National Journal of Physiology, Pharmacy and Pharmacology. 2017. 7:808–811 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L617689511 10.5455/njppp.2017.7.0410907042017 | X
322. | Manning, F.,Harris, K.,Duncan, R.,Walton, K.,Bracks, J.,Larby, L.,Vari, L.,Jukkola, K.,Bell, J.,Chan, M.,Batterham, M. Additional feeding assistance improves the energy and protein intakes of hospitalised elderly patients. A health services evaluation. Appetite. 2012. 59:471–7 https://www.ncbi.nlm.nih.gov/pubmed/22735333 22735333 | | X | | X
323. | Marcos-Forniol, E.,Meco, J. F.,Corbella, E.,Formiga, F.,Pinto, X. Secondary prevention programme of ischaemic heart disease in the elderly: A randomised clinical trial. Eur J Prev Cardiol. 2018. 25:278–286 https://www.ncbi.nlm.nih.gov/pubmed/29164902 29164902 | | X | | X | | | | X
324. | Marighela, T. F.,Genaro Pde, S.,Pinheiro, M. M.,Szejnfeld, V. L.,Kayser, C. Risk factors for body composition abnormalities in systemic sclerosis. Clin Rheumatol. 2013. 32:1037–44 https://www.ncbi.nlm.nih.gov/pubmed/23549639 23549639 | X | | | X | | | | X
325. | Marques, E. A.,Moreira, P.,Wanderley, F.,Pizarro, A. N.,Leao-Rosas, J. P.,Mota, J., Carvalho, J. Appendicular fat mass is positively associated with femoral neck bone mineral density in older women. Menopause. 2012. 19:311–8 https://www.ncbi.nlm.nih.gov/pubmed/22027941 22027941 | | X | | X
326. | Marques, E.,Wanderley, F.,Goncalves, D.,Coelho, M.,Viana, J.,Moreira, P.,Mota, J., Carvalho, J. A comparison of resistance and aerobic exercise training on physical ability, bone mineral density and osteoprotegerin in older women. Journal of bone and mineral research.. 2010. 25:S87 https://www.cochranelibrary.com/central/doi/10.1002/central/CN-01060907/full | X | X | | X
327. | Martin, H.,Aihie Sayer, A.,Jameson, K.,Syddall, H.,Dennison, E. M.,Cooper, C., Robinson, S. Does diet influence physical performance in community-dwelling older people? Findings from the Hertfordshire Cohort Study. Age Ageing. 2011. 40:181–6 https://www.ncbi.nlm.nih.gov/pubmed/21239409 21239409 | X
328. | Martin, I. S. M.,Barato, V. P.,Oliva, S. L.,Rodriguez, M.,Yurrita, L. C.,Cabanas, M. J. C.,Rojo, S. S.,de la Calle, L.,Diaz, E. A.,Santos, Y. Q.,Pascual, P. E.,Nieto, M. V., Vilar, E. G. Body Composition, Dietary, and Gustatory Function Assessment in People With Alzheimer’s Disease. Am J Alzheimers Dis Other Demen. 2018. 33:508–515 https://www.ncbi.nlm.nih.gov/pubmed/29916258 29916258 | X | | | | | | | X
329. | Martinez-Rodriguez, A.,Roche, E. Effect of satiety on body composition and anxiety in university athletes: cohort study. Nutr Hosp. 2017. 34:396–401 https://www.ncbi.nlm.nih.gov/pubmed/28421796 28421796 | | X
330. | McClure, R.,Villani, A. Greater adherence to a Mediterranean Diet is associated with better gait speed in older adults with type 2 diabetes mellitus. Clinical Nutrition ESPEN. 2019. #volume#:#pages# http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L2002056577 10.1016/j.clnesp.2019.05.009 | X | | | | | | | X
331. | McDonald, C.,Bauer, J.,Capra, S.,Coll, J. The muscle mass, omega-3, diet, exercise and lifestyle (MODEL) study - a randomised controlled trial for women who have completed breast cancer treatment. BMC Cancer. 2014. 14:264 https://www.ncbi.nlm.nih.gov/pubmed/24739260 24739260 | X | | | | | | | X
332. | McLean, R. R.,Mangano, K. M.,Hannan, M. T.,Kiel, D. P.,Sahni, S. Dietary Protein Intake Is Protective Against Loss of Grip Strength Among Older Adults in the Framingham Offspring Cohort. J Gerontol A Biol Sci Med Sci. 2016. 71:356–61 https://www.ncbi.nlm.nih.gov/pubmed/26525088 26525088 | | X
333. | McSwiney, F. T.,Wardrop, B.,Hyde, P. N.,Lafountain, R. A.,Volek, J. S.,Doyle, L. Keto-adaptation enhances exercise performance and body composition responses to training in endurance athletes. Metabolism: Clinical and Experimental. 2018. 81:25–34 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L619470973 10.1016/j.metabol.2017.10.010 29108901 | | | | | | | | X
334. | Mears, M.,Tussing-Humphreys, L.,Cerwinske, L.,Tangney, C.,Hughes, S. L.,Fitzgibbons, M.,Gomez-Perez, S. Associations between Alternate Healthy Eating Index-2010, Body Composition, Osteoarthritis Severity, and Interleukin-6 in Older Overweight and Obese African American Females with Self-Reported Osteoarthritis. Nutrients. 2018. 11:#pages# https://www.ncbi.nlm.nih.gov/pubmed/30583501 | X
335. | Meirelles, C.,Candido, T.,Gomes, P. S. Effects of short-term very low-carbohydrate or conventional diet on strength performance. J Sports Med Phys Fitness. 2010. 50:189–95 https://www.ncbi.nlm.nih.gov/pubmed/20585297 20585297 | | X | | X
336. | Mendonca, N.,Granic, A.,Mathers, J. C.,Hill, T. R.,Siervo, M.,Adamson, A. J., Jagger, C. Prevalence and determinants of low protein intake in very old adults: insights from the Newcastle 85+ Study. Eur J Nutr. 2018. 57:2713–2722 https://www.ncbi.nlm.nih.gov/pubmed/28948346 28948346 | X | | | X
337. | Meng, X.,Zhu, K.,Devine, A.,Kerr, D. A.,Binns, C. W.,Prince, R. L. A 5-year cohort study of the effects of high protein intake on lean mass and BMC in elderly postmenopausal women. J Bone Miner Res. 2009. 24:1827–34 https://www.ncbi.nlm.nih.gov/pubmed/19419320 19419320 | | | | X
338. | Merra, G.,Gratteri, S.,De Lorenzo, A.,Barrucco, S.,Perrone, M. A.,Avolio, E., Bernardini, S.,Marchetti, M.,Di Renzo, L. Effects of very-low-calorie diet on body composition, metabolic state, and genes expression: a randomized double-blind placebo-controlled trial. Eur Rev Med Pharmacol Sci. 2017. 21:329–345 https://www.ncbi.nlm.nih.gov/pubmed/28165552 28165552 | | | | X
339. | Merra, G.,Miranda, R.,Barrucco, S.,Gualtieri, P.,Mazza, M.,Moriconi, E.,Marchetti, M.,Chang, T. F.,De Lorenzo, A.,Di Renzo, L. Very-low-calorie ketogenic diet with aminoacid supplement versus very low restricted-calorie diet for preserving muscle mass during weight loss: a pilot double-blind study. Eur Rev Med Pharmacol Sci. 2016. 20:2613–21 https://www.ncbi.nlm.nih.gov/pubmed/27383313 27383313 | X | X | X
340. | Messier, S. P.,Loeser, R. F.,Mitchell, M. N.,Valle, G.,Morgan, T. P.,Rejeski, W. J.,Ettinger, W. H. Exercise and weight loss in obese older adults with knee osteoarthritis: a preliminary study. J Am Geriatr Soc. 2000. 48:1062–72 https://www.ncbi.nlm.nih.gov/pubmed/10983905 10983905 | | X
341. | Michalczyk, M.,Zajac, A.,Mikolajec, K.,Zydek, G.,Langfort, J. No Modification in Blood Lipoprotein Concentration but Changes in Body Composition after 4 Weeks of Low Carbohydrate Diet (LCD) Followed by 7 Days of Carbohydrate Loading in Basketball Players. J Hum Kinet. 2018. 65:125–137 https://www.ncbi.nlm.nih.gov/pubmed/30687425 30687425 | | | | | | | | X
342. | Mielgo-Ayuso, J.,Zourdos, M. C.,Calleja-Gonzalez, J.,Urdampilleta, A.,Ostojic, S. M. Dietary intake habits and controlled training on body composition and strength in elite female volleyball players during the season. Appl Physiol Nutr Metab. 2015. 40:827–34 https://www.ncbi.nlm.nih.gov/pubmed/26224330 26224330 | X | X | | | | | | X
343. | Milaneschi, Y.,Bandinelli, S.,Corsi, A. M.,Lauretani, F.,Paolisso, G.,Dominguez, L. J.,Semba, R. D.,Tanaka, T.,Abbatecola, A. M.,Talegawkar, S. A.,Guralnik, J. M., Ferrucci, L. Mediterranean diet and mobility decline in older persons. Exp Gerontol. 2011. 46:303–8 https://www.ncbi.nlm.nih.gov/pubmed/21111801 21111801 | | | | X
344. | Miller, G. D. Improved nutrient intake in older obese adults undergoing a structured diet and exercise intentional weight loss program. J Nutr Health Aging. 2010. 14:461–6 https://www.ncbi.nlm.nih.gov/pubmed/20617289 20617289 | | X | | X
345. | Miller, G. D.,Rejeski, W. J.,Williamson, J. D.,Morgan, T.,Sevick, M. A.,Loeser, R. F., Ettinger, W. H.,Messier, S. P. The Arthritis, Diet and Activity Promotion Trial (ADAPT): design, rationale, and baseline results. Control Clin Trials. 2003. 24:462–80 https://www.ncbi.nlm.nih.gov/pubmed/12865040 12865040 | X
346. | Milte, C. M.,Thorpe, M. G.,Crawford, D.,Ball, K.,McNaughton, S. A. Associations of diet quality with health-related quality of life in older Australian men and women. Exp Gerontol. 2015. 64:8–16 https://www.ncbi.nlm.nih.gov/pubmed/25639944 25639944 | | | | X
347. | Mitchell, C. J.,Milan, A. M.,Mitchell, S. M.,Zeng, N.,Ramzan, F.,Sharma, P., Knowles, S. O.,Roy, N. C.,Sjodin, A.,Wagner, K. H.,Cameron-Smith, D. The effects of dietary protein intake on appendicular lean mass and muscle function in elderly men: a 10-wk randomized controlled trial. Am J Clin Nutr. 2017. 106:1375–1383 https://www.ncbi.nlm.nih.gov/pubmed/29092886 29092886 | | X | X
348. | Miyatake, N.,Nishikawa, H.,Morishita, A.,Kunitomi, M.,Wada, J.,Suzuki, H.,Takahashi, K.,Makino, H.,Kira, S.,Fujii, M. Daily walking reduces visceral adipose tissue areas and improves insulin resistance in Japanese obese subjects. Diabetes Res Clin Pract. 2002. 58:101–7 https://www.ncbi.nlm.nih.gov/pubmed/12213351 12213351 | X | X
349. | Mohamad, H. A., Jr.,Suzana, S.,Noor Ibrahim, M. S.,Norshafarina, S. Relationship between Appetite, Food Intake and Body Composition among Elderly Malays from an Urban Residential Area in Kuala Lumpur, Malaysia. Malays J Nutr. 2010. 16:339–48 https://www.ncbi.nlm.nih.gov/pubmed/22691987 22691987 | X
350. | Mohammed, S. S.,Aghdassi, E.,Salit, I. E.,Avand, G.,Sherman, M.,Guindi, M., Heathcote, J. E.,Allard, J. P. HIV-positive patients with nonalcoholic fatty liver disease have a lower body mass index and are more physically active than HIV-negative patients. J Acquir Immune Defic Syndr. 2007. 45:432–8 https://www.ncbi.nlm.nih.gov/pubmed/17558337 17558337 | X | X | | X | | | | X
351. | Mohorko, N.,Cernelic-Bizjak, M.,Poklar-Vatovec, T.,Grom, G.,Kenig, S.,Petelin, A., Jenko-Praznikar, Z. Weight loss, improved physical performance, cognitive function, eating behavior, and metabolic profile in a 12-week ketogenic diet in obese adults. Nutr Res. 2019. 62:64–77 https://www.ncbi.nlm.nih.gov/pubmed/30803508 30803508 | X
352. | Mojtahedi, M. C.,Thorpe, M. P.,Karampinos, D. C.,Johnson, C. L.,Layman, D. K., Georgiadis, J. G.,Evans, E. M. The effects of a higher protein intake during energy restriction on changes in body composition and physical function in older women. J Gerontol A Biol Sci Med Sci. 2011. 66:1218–25 https://www.ncbi.nlm.nih.gov/pubmed/21798863 21798863 | | | | X
353. | Moon, K. T. Decreasing fall risk in older adults with nutritional intervention. American Family Physician. 2012. 86:676 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L365811917 | | X | | | X
354. | Moore, D. R.,Del Bel, N. C.,Nizi, K. I.,Hartman, J. W.,Tang, J. E.,Armstrong, D., Phillips, S. M. Resistance training reduces fasted- and fed-state leucine turnover and increases dietary nitrogen retention in previously untrained young men. J Nutr. 2007. 137:985–91 https://www.ncbi.nlm.nih.gov/pubmed/17374665 17374665 | X | X
355. | Moran, D. S.,Heled, Y.,Arbel, Y.,Israeli, E.,Finestone, A. S.,Evans, R. K.,Yanovich, R. Dietary intake and stress fractures among elite male combat recruits. J Int Soc Sports Nutr. 2012. 9:6 https://www.ncbi.nlm.nih.gov/pubmed/22413851 22413851 | | | | X
356. | Moreto, F.,de Oliveira, E. P.,Manda, R. M.,Torezan, G. A.,Teixeira, O.,Michelin, E., Burini, R. C. Pathological and behavioral risk factors for higher serum C-reactive protein concentrations in free-living adults--a Brazilian community-based study. Inflammation. 2013. 36:15–25 https://www.ncbi.nlm.nih.gov/pubmed/22865000 22865000 | X | X | | X
357. | Morris, M. S.,Jacques, P. F. Total protein, animal protein and physical activity in relation to muscle mass in middle-aged and older Americans. Br J Nutr. 2013. 109:1294–303 https://www.ncbi.nlm.nih.gov/pubmed/22856586 22856586 | X
358. | Moschonis, G.,Tanagra, S.,Koutsikas, K.,Nikolaidou, A.,Androutsos, O.,Manios, Y. Association between serum 25-hydroxyvitamin D levels and body composition in postmenopausal women: the postmenopausal Health Study. Menopause. 2009. 16:701–7 https://www.ncbi.nlm.nih.gov/pubmed/19276997 19276997 | X | X
359. | Motevalli, M. S.,Dalbo, V. J.,Attarzadeh, R. S.,Rashidlamir, A.,Tucker, P. S., Scanlan, A. T. The effect of rate of weight reduction on serum myostatin and follistatin concentrations in competitive wrestlers. Int J Sports Physiol Perform. 2015. 10:139–46 https://www.ncbi.nlm.nih.gov/pubmed/24911427 24911427 | | X | | X | | | | X
360. | Mulla, U. Z.,Cooper, R.,Mishra, G. D.,Kuh, D.,Stephen, A. M. Adult macronutrient intake and physical capability in the MRC National Survey of Health and Development. Age Ageing. 2013. 42:81–7 https://www.ncbi.nlm.nih.gov/pubmed/22923606 22923606 | | X
361. | Muller, K.,Morais, J.,Feine, J. Nutritional and anthropometric analysis of edentulous patients wearing implant overdentures or conventional dentures. Braz Dent J. 2008. 19:145–50 https://www.ncbi.nlm.nih.gov/pubmed/18568230 18568230 | | X | | X
362. | Munk, T.,Beck, A. M.,Holst, M.,Rosenbom, E.,Rasmussen, H. H.,Nielsen, M. A., Thomsen, T. Positive effect of protein-supplemented hospital food on protein intake in patients at nutritional risk: a randomised controlled trial. J Hum Nutr Diet. 2014. 27:122–32 https://www.ncbi.nlm.nih.gov/pubmed/24479388 24479388 | | | | | | | | X
363. | Murphy, C. H.,Saddler, N. I.,McGlory, C.,Devries, M. C.,Baker, S. K.,Phillips, S. M. Leucine supplementation enhances integrated myofibrillar protein synthesis in older men consuming lower and higher protein diets. Clinical nutrition (edinburgh, scotland). 2016. 35:S132- https://www.cochranelibrary.com/central/doi/10.1002/central/CN-01361469/full | | | | X | X
364. | Muscariello, E.,Nasti, G.,Siervo, M.,Di Maro, M.,Lapi, D.,D’Addio, G.,Colantuoni, A. Dietary protein intake in sarcopenic obese older women. Clin Interv Aging. 2016. 11:133–40 https://www.ncbi.nlm.nih.gov/pubmed/26917955 26917955 | | X
365. | Mustafa, J.,Ellison, R. C.,Singer, M. R.,Bradlee, M. L.,Kalesan, B.,Holick, M. F., Moore, L. L. Dietary Protein and Preservation of Physical Functioning Among Middle-Aged and Older Adults in the Framingham Offspring Study. Am J Epidemiol. 2018. 187:1411–1419 https://www.ncbi.nlm.nih.gov/pubmed/29590270 29590270 | | | | X
366. | Nabuco, H. C. G.,Tomeleri, C. M.,Fernandes, R. R.,Sugihara Junior, P.,Cavalcante, E. F.,Cunha, P. M.,Antunes, M.,Nunes, J. P.,Venturini, D.,Barbosa, D. S.,Burini, R. C.,Silva, A. M.,Sardinha, L. B.,Cyrino, E. S. Effect of whey protein supplementation combined with resistance training on body composition, muscular strength, functional capacity, and plasma-metabolism biomarkers in older women with sarcopenic obesity: A randomized, double-blind, placebo-controlled trial. Clinical Nutrition ESPEN. 2019. #volume#:#pages# http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L2001954541 10.1016/j.clnesp.2019.04.007 | | X | | | | | | X
367. | Nabuco, H. C. G.,Tomeleri, C. M.,Sugihara Junior, P.,Fernandes, R. R.,Cavalcante, E. F.,Venturini, D.,Barbosa, D. S.,Silva, A. M.,Sardinha, L. B.,Cyrino, E. S. Effects of pre- or post-exercise whey protein supplementation on body fat and metabolic and inflammatory profile in pre-conditioned older women: A randomized, double-blind, placebo-controlled trial. Nutr Metab Cardiovasc Dis. 2019. 29:290–300 https://www.ncbi.nlm.nih.gov/pubmed/30639252 30639252 | | X
368. | Nabuco, H. C.,Tomeleri, C. M.,Junior, P. S.,Fernandes, R. R.,Cavalcante, E. F., Nunes, J. P.,Cunha, P. F.,Dos Santos, L.,Cyrino, E. S. Effects of higher habitual protein intake on resistance-training-induced changes in body composition and muscular strength in untrained older women: a clinical trial study. Nutrition and health. 2019. #volume#:260106019838365 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L627046600 10.1177/0260106019838365 | | X
369. | Nagai, Y.,Kawanabe, S.,Fukuda, H.,Tanaka, Y. Changes of body composition after replacing dietary carbohydrate with a protein supplement in overweight Japanese subjects. Journal of diabetes investigation. 2018. 9:44- https://www.cochranelibrary.com/central/doi/10.1002/central/CN-01793199/full 28593750 | X | | | | X
370. | Nahas, P. C.,Rossato, L. T.,Martins, F. M.,Souza, A. P.,de Branco, F. M. S.,Carneiro, M. A. S.,Teixeira, K. R. C.,Orsatti, F. L.,de Oliveira, E. P. Moderate Increase in Protein Intake Promotes a Small Additional Improvement in Functional Capacity, But Not in Muscle Strength and Lean Mass Quality, in Postmenopausal Women Following Resistance Exercise: A Randomized Clinical Trial. Nutrients. 2019. 11:#pages# https://www.ncbi.nlm.nih.gov/pubmed/31200437 | | | | X
371. | Nahas, P.,Rossato, L.,De Branco, F.,Martins, F.,Souza, A.,Carneiro, M.,Orsatti, F., De Oliveira, E. Changes in lean mass is correlated with changes in muscle function only in postmenopausal women who consumed higher amounts of protein during resistance training protocol. Annals of nutrition & metabolism. 2017. 71:529- https://www.cochranelibrary.com/central/doi/10.1002/central/CN-01428820/full | | X | | | X
372. | Nahhas, R. W.,Choh, A. C.,Lee, M.,Cameron Chumlea, W. M.,Duren, D. L.,Siervogel, R. M.,Sherwood, R. J.,Towne, B.,Czerwinski, S. A. Bayesian longitudinal plateau model of adult grip strength. American Journal of Human Biology. 2010. 22:648–656 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L359681368 10.1002/ajhb.21057 20737612 | X | X
373. | Naidoo, R.,Coopoo, Y. The health and fitness profiles of nurses in KwaZulu-Natal. Curationis. 2007. 30:66–73 https://www.ncbi.nlm.nih.gov/pubmed/17703824 17703824 | X | X | | | | | X
374. | Nakamura, K.,Nishiwaki, T.,Ueno, K.,Yamamoto, M. Serum 25-hydroxyvitamin D levels and activities of daily living in noninstitutionalized elderly Japanese requiring care. J Bone Miner Metab. 2005. 23:488–94 https://www.ncbi.nlm.nih.gov/pubmed/16261457 16261457 | X | X
375. | Nascimento, M. A. D.,Gerage, A. M.,Silva, Drpd,Ribeiro, A. S.,Machado, Dgds, Pina, F. L. C.,Tomeleri, C. M.,Venturini, D.,Barbosa, D. S.,Mayhew, J. L.,Cyrino, E. S. Effect of resistance training with different frequencies and subsequent detraining on muscle mass and appendicular lean soft tissue, IGF-1, and testosterone in older women. Eur J Sport Sci. 2019. 19:199–207 https://www.ncbi.nlm.nih.gov/pubmed/30016192 30016192 | | X | | X
376. | Nasreddine, L.,Akika, R.,Mailhac, A.,Tamim, H.,Zgheib, N. K. The Interaction between Genetic Polymorphisms in FTO and TCF7L2 Genes and Dietary Intake with Regard to Body Mass and Composition: An Exploratory Study. J Pers Med. 2019. 9:#pages# https://www.ncbi.nlm.nih.gov/pubmed/30764585 | X
377. | Nazare, J. A.,Smith, J.,Borel, A. L.,Almeras, N.,Tremblay, A.,Bergeron, J.,Poirier, P.,Despres, J. P. Changes in both global diet quality and physical activity level synergistically reduce visceral adiposity in men with features of metabolic syndrome. J Nutr. 2013. 143:1074–83 https://www.ncbi.nlm.nih.gov/pubmed/23719226 23719226 | | | | X
378. | Nct, Impact of Interventions With a Diet and Exercise on the Cardio-metabolic Status in Multi-risk Population. Https://clinicaltrials.gov/show/nct03701425. 2018. #volume#:#pages# https://www.cochranelibrary.com/central/doi/10.1002/central/CN-01663999/full | | X | | | X
379. | Nct, Mediterranean Diet, Circuit Resistance Training, Empagliflozin in Elderly With Type 2 Diabetes: a Study Protocol. Https://clinicaltrials.gov/show/nct03560375. 2018. #volume#:#pages# https://www.cochranelibrary.com/central/doi/10.1002/central/CN-01660423/full | X | | | | X | | | X
380. | Nct, Diet and Muscle Function In Older Adults. Https://clinicaltrials.gov/show/nct02069314. 2014. #volume#:#pages# https://www.cochranelibrary.com/central/doi/10.1002/central/CN-01543860/full | X | | | | X
381. | Nct, Effects of High Protein Diet on Muscle Mass, Strength, and Physical Performance in Postmenopausal Women. Https://clinicaltrials.gov/show/nct03652584. 2018. #volume#:#pages# https://www.cochranelibrary.com/central/doi/10.1002/central/CN-01662789/full | X | | | | X
382. | Neelemaat, F.,Bosmans, J. E.,Thijs, A.,Seidell, J. C.,van Bokhorst-de van der Schueren, M. A. E. Post-Discharge Nutritional Support in Malnourished Elderly Individuals Improves Functional Limitations. Journal of the American Medical Directors Association. 2011. 12:295–301 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L361656698 10.1016/j.jamda.2010.12.005 21527171 | | X
383. | Negro, M.,Vandoni, M.,Ottobrini, S.,Codrons, E.,Correale, L.,Buonocore, D., Marzatico, F. Protein supplementation with low fat meat after resistance training: Effects on body composition and strength. Nutrients. 2014. 6:3040–3049 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L373710926 10.3390/nu6083040 25093275 | X | X
384. | Neville, C. E.,Young, I. S.,Gilchrist, S. E.,McKinley, M. C.,Gibson, A.,Edgar, J. D., Woodside, J. V. Effect of increased fruit and vegetable consumption on physical function and muscle strength in older adults. Age (Dordr). 2013. 35:2409–22 https://www.ncbi.nlm.nih.gov/pubmed/23543264 23543264 | | X
385. | Nilsson, A.,Montiel Rojas, D.,Kadi, F. Impact of Meeting Different Guidelines for Protein Intake on Muscle Mass and Physical Function in Physically Active Older Women. Nutrients. 2018. 10:#pages# https://www.ncbi.nlm.nih.gov/pubmed/30149519 | X
386. | Norton, C.,Toomey, C.,McCormack, W. G.,Francis, P.,Saunders, J.,Kerin, E., Jakeman, P. Protein Supplementation at Breakfast and Lunch for 24 Weeks beyond Habitual Intakes Increases Whole-Body Lean Tissue Mass in Healthy Older Adults. J Nutr. 2016. 146:65–9 https://www.ncbi.nlm.nih.gov/pubmed/26581685 26581685 | | X
387. | Norton, C.,Toomey, C.,McCormack, W.,Francis, P.,Jakeman, P. Effect of 6 month supplemental milk protein intake on lean tissue mass in healthy adults aged 50 to 70 years. Proceedings of the nutrition society. 2015. 74:#pages# https://www.cochranelibrary.com/central/doi/10.1002/central/CN-01407723/full | | X
388. | Novakova, K.,Kummer, O.,Bouitbir, J.,Stoffel, S. D.,Hoerler-Koerner, U.,Bodmer, M.,Roberts, P.,Urwyler, A.,Ehrsam, R.,Krähenbühl, S. Effect of l-carnitine supplementation on the body carnitine pool, skeletal muscle energy metabolism and physical performance in male vegetarians. European Journal of Nutrition. 2016. 55:207–217 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L602140696 10.1007/s00394-015-0838-9 25612929 | | X | | X
389. | Nowson, C.,O’Connell, S.,Mundell, N.,Grimes, C.,Dunstan, D.,Daly, R. A protein-enriched diet favourably affects cardiovascular health in elderly women undertaking progressive resistance training. Annals of nutrition & metabolism. 2013. 63:657 https://www.cochranelibrary.com/central/doi/10.1002/central/CN-01025195/full | X | | | | X
390. | Nygard, L. K.,Mundal, I.,Dahl, L.,Rokstad, A. M. M. Nutrition and sarcopenia in frail elderly: a randomized controlled trial of the effects of marine protein hydrolysates to improve physical performance. Journal of cachexia, sarcopenia and muscle. 2017. 8:181- https://www.cochranelibrary.com/central/doi/10.1002/central/CN-01361590/full | X | X | | | X
391. | Ocobock, C. J. Body fat attenuates muscle mass catabolism among physically active humans in temperate and cold high altitude environments. Am J Hum Biol. 2017. 29:#pages# https://www.ncbi.nlm.nih.gov/pubmed/28467016 | | X
392. | Ogata Medel, M.,Lozada Mellado, M.,Garcia Morales, J. M.,Hinojosa Azaola, A.,Morales Herrero, N.,Llorente, L.,Alcocer Varela, J.,Pineda Juarez, J. A.,Cervantes Gaytan, R.,Castillo Martinez, L. Effect of a dynamic exercise program in combination with a mediterranean diet in weight and handgrip strength in women with rheumatoid arthritis. Clinical and experimental rheumatology. 2018. 36:S78- https://www.cochranelibrary.com/central/doi/10.1002/central/CN-01605063/full | X | X | | | X | | | X
393. | Oh, C.,Jeon, B. H.,Reid Storm, S. N.,Jho, S.,No, J. K. The most effective factors to offset sarcopenia and obesity in the older Korean: Physical activity, vitamin D, and protein intake. Nutrition. 2017. 33:169–173 https://www.ncbi.nlm.nih.gov/pubmed/27717662 27717662 | X | X
394. | Oh, C.,Jho, S.,No, J. K.,Kim, H. S. Body composition changes were related to nutrient intakes in elderly men but elderly women had a higher prevalence of sarcopenic obesity in a population of Korean adults. Nutr Res. 2015. 35:1–6 https://www.ncbi.nlm.nih.gov/pubmed/25524331 25524331 | X
395. | Oh, C.,No, J. K.,Kim, H. S. Dietary pattern classifications with nutrient intake and body composition changes in Korean elderly. Nutr Res Pract. 2014. 8:192–7 https://www.ncbi.nlm.nih.gov/pubmed/24741404 24741404 | X
396. | Okita, K.,Takada, S.,Kinugawa, S. Very low-carbohydrate diet can effectively reduce weight without deterioration in physical fitness. Journal of the hong kong college of cardiology. 2016. 24:A32- https://www.cochranelibrary.com/central/doi/10.1002/central/CN-01789343/full | X | | | | X
397. | Ordonez, A. M.,Madalozzo Schieferdecker, M. E.,Cestonaro, T.,Cardoso Neto, J., Ligocki Campos, A. C. Nutritional status influences the length of stay and clinical outcomes in patients hospitalized in internal medicine wards. Nutr Hosp. 2013. 28:1313–20 https://www.ncbi.nlm.nih.gov/pubmed/23889658 23889658 | | X | | | | | | X
398. | Orsatti, F. L.,Maesta, N.,de Oliveira, E. P.,Nahas Neto, J.,Burini, R. C.,Nunes, P. R. P.,Souza, A. P.,Martins, F. M.,Nahas, E. P. Adding Soy Protein to Milk Enhances the Effect of Resistance Training on Muscle Strength in Postmenopausal Women. J Diet Suppl. 2018. 15:140–152 https://www.ncbi.nlm.nih.gov/pubmed/28604135 28604135 | | X
399. | Ortola, R.,Garcia-Esquinas, E.,Leon-Munoz, L. M.,Guallar-Castillon, P.,Valencia-Martin, J. L.,Galan, I.,Rodriguez-Artalejo, F. Patterns of Alcohol Consumption and Risk of Frailty in Community-dwelling Older Adults. J Gerontol A Biol Sci Med Sci. 2016. 71:251–8 https://www.ncbi.nlm.nih.gov/pubmed/26297937 26297937 | | X | | X
400. | Osella, A. R.,Colaianni, G.,Correale, M.,Pesole, P. L.,Bruno, I.,Buongiorno, C., Deflorio, V.,Leone, C. M.,Colucci, S. C.,Grano, M.,Giannelli, G. Irisin Serum Levels in Metabolic Syndrome Patients Treated with Three Different Diets: A Post-Hoc Analysis from a Randomized Controlled Clinical Trial. Nutrients. 2018. 10:#pages# https://www.ncbi.nlm.nih.gov/pubmed/29958455 | | | | X | | | | X
401. | Otsuka, R.,Kato, Y.,Nishita, Y.,Tange, C.,Nakamoto, M.,Tomida, M.,Imai, T.,Ando, F.,Shimokata, H.,Suzuki, T. Dietary diversity and 14-year decline in higher-level functional capacity among middle-aged and elderly Japanese. Nutrition. 2016. 32:784–9 https://www.ncbi.nlm.nih.gov/pubmed/27068882 27068882 | | | | X
402. | Otsuka, R.,Tange, C.,Tomida, M.,Nishita, Y.,Kato, Y.,Yuki, A.,Ando, F.,Shimokata, H.,Arai, H. Dietary factors associated with the development of physical frailty in community-dwelling older adults. J Nutr Health Aging. 2019. 23:89–95 https://www.ncbi.nlm.nih.gov/pubmed/30569075 30569075 | | X
403. | Ottestad, I.,Lovstad, A. T.,Gjevestad, G. O.,Hamarsland, H.,Saltyte Benth, J., Andersen, L. F.,Bye, A.,Biong, A. S.,Retterstol, K.,Iversen, P. O.,Raastad, T.,Ulven, S. M.,Holven, K. B. Intake of a Protein-Enriched Milk and Effects on Muscle Mass and Strength. A 12-Week Randomized Placebo Controlled Trial among Community-Dwelling Older Adults. J Nutr Health Aging. 2017. 21:1160–1169 https://www.ncbi.nlm.nih.gov/pubmed/29188875 29188875 | | X
404. | Panagaria, N.,Varma, K.,Nijhawan, S.,Mathur, A.,Rai, R. R. Quality of life and nutritional status in alcohol addicts and patients with chronic liver disease. Trop Gastroenterol. 2007. 28:171–5 https://www.ncbi.nlm.nih.gov/pubmed/18416348 18416348 | X | X | | X | | | | X
405. | Paoli, A.,Grimaldi, K.,D’Agostino, D.,Cenci, L.,Moro, T.,Bianco, A.,Palma, A. Ketogenic diet does not affect strength performance in elite artistic gymnasts. J Int Soc Sports Nutr. 2012. 9:34 https://www.ncbi.nlm.nih.gov/pubmed/22835211 22835211 | | | | | | | | X
406. | Paoli, A.,Pacelli, Q. F.,Cancellara, P.,Toniolo, L.,Moro, T.,Canato, M.,Miotti, D.,Neri, M.,Morra, A.,Quadrelli, M.,Reggiani, C. Protein Supplementation Does Not Further Increase Latissimus Dorsi Muscle Fiber Hypertrophy after Eight Weeks of Resistance Training in Novice Subjects, but Partially Counteracts the Fast-to-Slow Muscle Fiber Transition. Nutrients. 2016. 8:#pages# https://www.ncbi.nlm.nih.gov/pubmed/27258300 | | X
407. | Paoli, A.,Pacelli, Q. F.,Neri, M.,Toniolo, L.,Cancellara, P.,Canato, M.,Moro, T., Quadrelli, M.,Morra, A.,Faggian, D.,Plebani, M.,Bianco, A.,Reggiani, C. Protein supplementation increases Postexercise plasma Myostatin concentration after 8 weeks of resistance training in young physically active subjects. Journal of Medicinal Food. 2015. 18:137–143 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L601208657 10.1089/jmf.2014.0004 25133710 | | X | | | | | | X
408. | Park, S. Change in physical performance in older women: role of protein supplement, diet, and obesity. Journal of the american geriatrics society. 2014. 62:S184- https://www.cochranelibrary.com/central/doi/10.1002/central/CN-01010375/full | X | | | | X
409. | Park, S.,Na, W.,Sohn, C. Relationship between osteosarcopenic obesity and dietary inflammatory index in postmenopausal Korean women: 2009 to 2011 Korea National Health and Nutrition Examination Surveys. J Clin Biochem Nutr. 2018. 63:211–216 https://www.ncbi.nlm.nih.gov/pubmed/30487671 30487671 | X
410. | Park, Y.,Choi, J. E.,Hwang, H. S. Protein supplementation improves muscle mass and physical performance in undernourished prefrail and frail elderly subjects: a randomized, double-blind, placebo-controlled trial. Am J Clin Nutr. 2018. 108:1026–1033 https://www.ncbi.nlm.nih.gov/pubmed/30475969 30475969 | | X
411. | Parr, E. B.,Coffey, V. G.,Burke, L. M.,Phillips, S. M.,Hawley, J. A. Effect of increased dairy consumption on weight loss during 16 weeks of energy restriction and exercise training. International journal of sport nutrition and exercise metabolism. Conference: 2014 international sports and exercise nutrition conference, ISENC 2014. United kingdom. 2015. 25:1–2 https://www.cochranelibrary.com/central/doi/10.1002/central/CN-01669755/full | | | | | X
412. | Parsons, T. J.,Papachristou, E.,Atkins, J. L.,Papacosta, O.,Ash, S.,Lennon, L. T., Whincup, P. H.,Ramsay, S. E.,Wannamethee, S. G. Physical frailty in older men: prospective associations with diet quality and patterns. Age Ageing. 2019. 48:355–360 https://www.ncbi.nlm.nih.gov/pubmed/30668624 30668624 | | | | X
413. | Parsons, T. J.,Papachristou, E.,Atkins, J. L.,Papacosta, O.,Ash, S.,Lennon, L. T., Whincup, P. H.,Ramsay, S. E.,Wannamethee, S. G. Healthier diet quality and dietary patterns are associated with lower risk of mobility limitation in older men. Eur J Nutr. 2019. 58:2335–2343 https://www.ncbi.nlm.nih.gov/pubmed/30039434 30039434 | | | | X
414. | Pasiakos, S. M.,Cao, J. J.,Margolis, L. M.,Sauter, E. R.,Whigham, L. D.,McClung, J. P.,Rood, J. C.,Carbone, J. W.,Combs, G. F., Jr.,Young, A. J. Effects of high-protein diets on fat-free mass and muscle protein synthesis following weight loss: a randomized controlled trial. Faseb j. 2013. 27:3837–47 https://www.ncbi.nlm.nih.gov/pubmed/23739654 23739654 | | | | X
415. | Penteado, Vsdr,Castro, C. H. M.,Pinheiro, M. M.,Santana, M.,Bertolino, S.,de Mello, M. T.,Szejnfeld, V. L. Diet, body composition, and bone mass in well-trained cyclists. J Clin Densitom. 2010. 13:43–50 https://www.ncbi.nlm.nih.gov/pubmed/19942468 19942468 | | X | | X | | | | X
416. | Perala, M. M.,von Bonsdorff, M. B.,Mannisto, S.,Salonen, M. K.,Simonen, M., Kanerva, N.,Rantanen, T.,Pohjolainen, P.,Eriksson, J. G. The healthy Nordic diet predicts muscle strength 10 years later in old women, but not old men. Age Ageing. 2017. 46:588–594 https://www.ncbi.nlm.nih.gov/pubmed/28338859 28338859 | | | | X
417. | Perala, M. M.,von Bonsdorff, M.,Mannisto, S.,Salonen, M. K.,Simonen, M.,Kanerva, N.,Pohjolainen, P.,Kajantie, E.,Rantanen, T.,Eriksson, J. G. A healthy Nordic diet and physical performance in old age: findings from the longitudinal Helsinki Birth Cohort Study. Br J Nutr. 2016. 115:878–86 https://www.ncbi.nlm.nih.gov/pubmed/26785760 26785760 | | | | X
418. | Perez, L. M.,Enfedaque-Montes, M. B.,Cesari, M.,Soto-Bagaria, L.,Gual, N.,Burbano, M. P.,Tarazona-Santabalbina, F. J.,Casas, R. M.,Diaz, F.,Martin, E.,Gomez, A.,Orfila, F.,Inzitari, M. A Community Program of Integrated Care for Frail Older Adults: +AGIL Barcelona. J Nutr Health Aging. 2019. 23:710–716 https://www.ncbi.nlm.nih.gov/pubmed/31560028 31560028 | | X
419. | Perez-Tasigchana, R. F.,Leon-Munoz, L. M.,Lopez-Garcia, E.,Banegas, J. R., Rodriguez-Artalejo, F.,Guallar-Castillon, P. Mediterranean Diet and Health-Related Quality of Life in Two Cohorts of Community-Dwelling Older Adults. PLoS One. 2016. 11:e0151596 https://www.ncbi.nlm.nih.gov/pubmed/27008160 27008160 | | | | X
420. | Peterson, M. J. The Risk Factors of Performance-Based Early Frailty in Midlife and Older Age. Gerontology and Geriatric Medicine. 2018. 4:#pages# http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L623248860 10.1177/2333721418770035 | | X
421. | Pétervári, E.,Soós, S.,Székely, M.,Balaskó, M. Alterations in the peptidergic regulation of energy balance in the course of aging. Current Protein and Peptide Science. 2011. 12:316–324 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L362082220 10.2174/138920311795906709 21574955 | X | X
422. | Petrofsky, J. S.,Ramseyn, K.,Patel, A.,Batt, J.,Prowse, M.,Bains, G. S.,Gunda, S., Sharma, A. The effect of a diet and exercise program with a mini medicine ball on cardiovascular fitness, weight loss, and strength. Journal of Applied Research. 2008. 8:116–129 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L352138191 | X | X
423. | Phinney, S. D. Ketogenic diets and physical performance. Nutr Metab (Lond). 2004. 1:2 https://www.ncbi.nlm.nih.gov/pubmed/15507148 15507148 | X
424. | Pilgrim, A. L.,Baylis, D.,Jameson, K. A.,Cooper, C.,Sayer, A. A.,Robinson, S. M., Roberts, H. C. Measuring appetite with the simplified nutritional appetite questionnaire identifies hospitalised older people at risk of worse health outcomes. Journal of Nutrition, Health and Aging. 2015. #volume#:#pages# http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L604329381 10.1007/s12603-015-0533-9 | | X | | X
425. | Pilis, K.,Pilis, A.,Stec, K.,Pilis, W.,Langfort, J.,Letkiewicz, S.,Michalski, C.,Czuba, M.,Zych, M.,Chalimoniuk, M. Three-Year Chronic Consumption of Low-Carbohydrate Diet Impairs Exercise Performance and Has a Small Unfavorable Effect on Lipid Profile in Middle-Aged Men. Nutrients. 2018. 10:#pages# https://www.ncbi.nlm.nih.gov/pubmed/30518095 | X
426. | Pilleron, S.,Ajana, S.,Jutand, M. A.,Helmer, C.,Dartigues, J. F.,Samieri, C.,Feart, C. Dietary Patterns and 12-Year Risk of Frailty: Results From the Three-City Bordeaux Study. J Am Med Dir Assoc. 2017. 18:169–175 https://www.ncbi.nlm.nih.gov/pubmed/27847264 27847264 | | | | X
427. | Pilleron, S.,Peres, K.,Jutand, M. A.,Helmer, C.,Dartigues, J. F.,Samieri, C.,Feart, C. Dietary patterns and risk of self-reported activity limitation in older adults from the Three-City Bordeaux Study. Br J Nutr. 2018. 120:549–556 https://www.ncbi.nlm.nih.gov/pubmed/29987992 29987992 | | | | X
428. | Pineda-Juarez, J. A.,Ogata-Medel, M.,Lozada-Mellado, M.,Castillo-Martinez, L.,Hinojosa-Azaola, A.,Gonzalez-Contreras, M.,Cervantes-Gaytan, R.,Garcia-Morales, J. M.,Alcocer-Varela, J.,Orea-Tejeda, A.,., Effect of a dynamic exercise program in combination with a mediterranean diet in strength, joint mobility and disease activity in women with rheumatoid arthritis. Arthritis & rheumatology. 2016. 68:3303–3304 https://www.cochranelibrary.com/central/doi/10.1002/central/CN-01293189/full | | X | | | | | | X
429. | Pistone, G.,Marino, A.,Leotta, C.,Dell’Arte, S.,Finocchiaro, G.,Malaguarnera, M. Levocarnitine administration in elderly subjects with rapid muscle fatigue: effect on body composition, lipid profile and fatigue. Drugs Aging. 2003. 20:761–7 https://www.ncbi.nlm.nih.gov/pubmed/12875611 12875611 | | X
430. | Pluijm, S. M. F.,Smit, J. H.,Tromp, E. A. M.,Stel, V. S.,Deeg, D. J. H.,Bouter, L. M., Lips, P. A risk profile for identifying community-dwelling elderly with a high risk of recurrent falling: Results of a 3-year prospective study. Osteoporosis International. 2006. 17:417–425 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L43461131 10.1007/s00198-005-0002-0 16416256 | | X | | X
431. | Porter Starr, K. N.,Orenduff, M.,McDonald, S. R.,Mulder, H.,Sloane, R.,Pieper, C. F.,Bales, C. W. Influence of Weight Reduction and Enhanced Protein Intake on Biomarkers of Inflammation in Older Adults with Obesity. J Nutr Gerontol Geriatr. 2019. 38:33–49 https://www.ncbi.nlm.nih.gov/pubmed/30810500 30810500 | | | | X
432. | Porter Starr, K. N.,Pieper, C. F.,Orenduff, M. C.,McDonald, S. R.,McClure, L. B.,Zhou, R.,Payne, M. E.,Bales, C. W. Improved Function With Enhanced Protein Intake per Meal: A Pilot Study of Weight Reduction in Frail, Obese Older Adults. J Gerontol A Biol Sci Med Sci. 2016. 71:1369–75 https://www.ncbi.nlm.nih.gov/pubmed/26786203 26786203 | | | | X
433. | Provan, M.,Mander, T. Mobility, exercise, nutrition and healthy ageing to avoid sarcopenia. Post Reproductive Health. 2018. 24:98–102 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L622705749 10.1177/2053369118773240 29925301 | X
434. | Pujos-Guillot, E.,Pétéra, M.,Jacquemin, J.,Centeno, D.,Lyan, B.,Montoliu, I.,Madej, D.,Pietruszka, B.,Fabbri, C.,Santoro, A.,Brzozowska, A.,Franceschi, C.,Comte, B. Identification of Pre-frailty Sub-Phenotypes in Elderly Using Metabolomics. Frontiers in Physiology. 2019. 10:#pages# http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L627617697 10.3389/fphys.2018.01903 | | X | | X
435. | Puranen, T. M.,Verho, J.,Suominen, M. H. Nutritional intervention among geriatric patients after discharge-baseline findings. European geriatric medicine. 2016. 7:S153- https://www.cochranelibrary.com/central/doi/10.1002/central/CN-01252722/full | X | | | | X
436. | Purcell, S.,Thornberry, R.,Elliott, S. A.,Panton, L.,Ormsbee, M. J.,Vieira, E. R.,Kim, J. S.,Prado, C. M. Body Composition, Strength, and Dietary Intake of Patients with Hip or Knee Osteoarthritis. Can J Diet Pract Res. 2016. 77:98–102 https://www.ncbi.nlm.nih.gov/pubmed/26568150 26568150 | X | X
437. | R. B. R. sbbvp Efect of Resistance Exercise Volume on Body Composition, Physical Performance, Metabolic, Hormonal and Inflammatory Profile in Postmenopausal Pre Sarcopenic Women. Http://www.who.int/trialsearch/trial2.aspx? Trialid=rbr-8sbbvp. 2015. #volume#:#pages# https://www.cochranelibrary.com/central/doi/10.1002/central/CN-01847378/full | X | | | | X
438. | Racette, S. B.,Deusinger, S. S.,Strube, M. J.,Highstein, G. R.,Deusinger, R. H. Weight changes, exercise, and dietary patterns during freshman and sophomore years of college. J Am Coll Health. 2005. 53:245–51 https://www.ncbi.nlm.nih.gov/pubmed/15900988 15900988 | | X | | X
439. | Radavelli-Bagatini, S.,Zhu, K.,Lewis, J. R.,Prince, R. L. Dairy food intake, peripheral bone structure, and muscle mass in elderly ambulatory women. J Bone Miner Res. 2014. 29:1691–700 https://www.ncbi.nlm.nih.gov/pubmed/24443390 24443390 | X
440. | Rahi, B.,Ajana, S.,Tabue-Teguo, M.,Dartigues, J. F.,Peres, K.,Feart, C. High adherence to a Mediterranean diet and lower risk of frailty among French older adults community-dwellers: Results from the Three-City-Bordeaux Study. Clin Nutr. 2018. 37:1293–1298 https://www.ncbi.nlm.nih.gov/pubmed/28629899 28629899 | | | | X
441. | Rahi, B.,Morais, J. A.,Dionne, I. J.,Gaudreau, P.,Payette, H.,Shatenstein, B. The combined effects of diet quality and physical activity on maintenance of muscle strength among diabetic older adults from the NuAge cohort. Exp Gerontol. 2014. 49:40–6 https://www.ncbi.nlm.nih.gov/pubmed/24269377 24269377 | | | | | | | | X
442. | Rahi, B.,Morais, J. A.,Gaudreau, P.,Payette, H.,Shatenstein, B. Energy and protein intakes and their association with a decline in functional capacity among diabetic older adults from the NuAge cohort. Eur J Nutr. 2016. 55:1729–39 https://www.ncbi.nlm.nih.gov/pubmed/26179475 26179475 | | X | | | | | | X
443. | Ramel, A.,Arnarson, A.,Geirsdottir, O. G.,Jonsson, P. V.,Thorsdottir, I. Glomerular filtration rate after a 12-wk resistance exercise program with post-exercise protein ingestion in community dwelling elderly. Nutrition. 2013. 29:719–23 https://www.ncbi.nlm.nih.gov/pubmed/23317926 23317926 | | X | | X
444. | Rasmussen, F.,Kark, M.,Tholin, S.,Karnehed, N.,Tynelius, P. The Swedish Young Male Twins Study: a resource for longitudinal research on risk factors for obesity and cardiovascular diseases. Twin Res Hum Genet. 2006. 9:883–9 https://www.ncbi.nlm.nih.gov/pubmed/17254425 17254425 | X
445. | Ren, Z.,Huang, C.,Momma, H.,Cui, Y.,Niu, K.,Sugiyama, S.,Nanno, M.,Nagatomi, R. High Tomato and Tomato Product Consumption is Protective Against the Decline in Handgrip Strength Among Japanese Adults: The Oroshisho Study. J Epidemiol. 2018. 28:397–403 https://www.ncbi.nlm.nih.gov/pubmed/29681560 29681560 | | X
446. | Rikkonen, T.,Sirola, J.,Salovaara, K.,Tuppurainen, M.,Jurvelin, J. S.,Honkanen, R.,Kroger, H. Muscle strength and body composition are clinical indicators of osteoporosis. Calcif Tissue Int. 2012. 91:131–8 https://www.ncbi.nlm.nih.gov/pubmed/22733383 22733383 | | X | | X
447. | Robinson, A. T.,Migdal, K. U.,Babcock, M. C.,Watso, J. C.,Wenner, M. M.,Stocker, S. D.,Farquhar, W. B. The effects of aerobic fitness on blood pressure reactivity during controlled low and high sodium diets. FASEB journal. 2018. 32:#pages# https://www.cochranelibrary.com/central/doi/10.1002/central/CN-01613740/full | | X | | X | X
448. | Robinson, S. M.,Jameson, K. A.,Batelaan, S. F.,Martin, H. J.,Syddall, H. E.,Dennison, E. M.,Cooper, C.,Sayer, A. A. Diet and its relationship with grip strength in community-dwelling older men and women: the Hertfordshire cohort study. J Am Geriatr Soc. 2008. 56:84–90 https://www.ncbi.nlm.nih.gov/pubmed/18005355 18005355 | | | | X
449. | Robinson, S. M.,Simmonds, S. J.,Jameson, K. A.,Syddall, H. E.,Dennison, E. M., Cooper, C.,Sayer, A. A. Muscle strength in older community-dwelling men is related to type of milk feeding in infancy. J Gerontol A Biol Sci Med Sci. 2012. 67:990–6 https://www.ncbi.nlm.nih.gov/pubmed/22421706 22421706 | X | X
450. | Robinson, S. M.,Westbury, L. D.,Cooper, R.,Kuh, D.,Ward, K.,Syddall, H. E.,Sayer, A. A.,Cooper, C. Adult Lifetime Diet Quality and Physical Performance in Older Age: Findings From a British Birth Cohort. J Gerontol A Biol Sci Med Sci. 2018. 73:1532–1537 https://www.ncbi.nlm.nih.gov/pubmed/29040508 29040508 | X
451. | Robitaille, J.,Houde, A.,Lemieux, S.,Perusse, L.,Gaudet, D.,Vohl, M. C. Variants within the muscle and liver isoforms of the carnitine palmitoyltransferase I (CPT1) gene interact with fat intake to modulate indices of obesity in French-Canadians. J Mol Med (Berl). 2007. 85:129–37 https://www.ncbi.nlm.nih.gov/pubmed/17089095 17089095 | X | X
452. | Rocha, J. S.,Ogando, B.,Rocha, M. S.,Moreira, M. H.,Gabriel, R.,Reis, V. Impact of a 12-month exercise program and hormone therapy (HT) on the body composition of postmenopausal women. Menopause (new york, N.Y.). 2012. 19:1396- https://www.cochranelibrary.com/central/doi/10.1002/central/CN-01008526/full | | X
453. | Rodriguez-Rejon, A. I.,Ruiz-Lopez, M. D.,Artacho, R. Dietary Intake and Associated Factors in Long-Term Care Homes in Southeast Spain. Nutrients. 2019. 11:#pages# https://www.ncbi.nlm.nih.gov/pubmed/30691005 | X
454. | Rom, O.,Reznick, A. Z.,Keidar, Z.,Karkabi, K.,Aizenbud, D. Smoking cessation-related weight gain--beneficial effects on muscle mass, strength and bone health. Addiction. 2015. 110:326–35 https://www.ncbi.nlm.nih.gov/pubmed/25312589 25312589 | | X
455. | Roque, M.,Salva, A.,Vellas, B. Malnutrition in community-dwelling adults with dementia (Nutrialz Trial). Journal of Nutrition, Health and Aging. 2013. 17:295–299 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L52270335 10.1007/s12603-012-0401-9 | X
456. | Rosenberger, C.,Rechsteiner, M.,Dietsche, R.,Breidert, M. Energy and protein intake in 330 geriatric orthopaedic patients: Are the current nutrition guidelines applicable?. Clinical Nutrition ESPEN. 2019. 29:86–91 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L2001382878 10.1016/j.clnesp.2018.11.016 30661706 | X | X | | X
457. | Rosendahl, E.,Lindelöf, N.,Littbrand, H.,Yifter-Lindgren, E.,Lundin-Olsson, L., Håglin, L.,Gustafson, Y.,Nyberg, L. High-intensity functional exercise program and protein-enriched energy supplement for older persons dependent in activities of daily living: A randomised controlled trial. Australian Journal of Physiotherapy. 2006. 52:105–113 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L43971018 10.1016/S0004-9514(06)70045-9 | | X
458. | Roth, S. M.,Zmuda, J. M.,Cauley, J. A.,Shea, P. R.,Ferrell, R. E. Vitamin D receptor genotype is associated with fat-free mass and sarcopenia in elderly men. J Gerontol A Biol Sci Med Sci. 2004. 59:10–5 https://www.ncbi.nlm.nih.gov/pubmed/14718481 14718481 | | X
459. | Roubenoff, R.,Walsmith, J.,Lundgren, N.,Snydman, L.,Dolnikowski, G. J.,Roberts, S. Low physical activity reduces total energy expenditure in women with rheumatoid arthritis: implications for dietary intake recommendations. Am J Clin Nutr. 2002. 76:774–9 https://www.ncbi.nlm.nih.gov/pubmed/12324290 12324290 | | X
460. | Rouffet, D.,Villars, C.,Fissoune, R.,Sappey-Marinier, D.,Laville, M.,Ibarrola, D., Sothier, M.,Monnet, M. F.,Ovize, M.,Bonnefoy, M.,Boesch, C.,Canet-Soulas, E. Intramyocellular lipid variations in active older men: relationship with aerobic fitness. Acta Physiol (Oxf). 2013. 207:516–23 https://www.ncbi.nlm.nih.gov/pubmed/23217190 23217190 | X | X | | X
461. | Rozenek, R.,Ward, P.,Long, S.,Garhammer, J. Effects of high-calorie supplements on body composition and muscular strength following resistance training. J Sports Med Phys Fitness. 2002. 42:340–7 https://www.ncbi.nlm.nih.gov/pubmed/12094125 12094125 | | X
462. | Ryberg, M.,Sandberg, S.,Mellberg, C.,Stegle, O.,Lindahl, B.,Larsson, C.,Hauksson, J.,Olsson, T. A Palaeolithic-type diet causes strong tissue-specific effects on ectopic fat deposition in obese postmenopausal women. J Intern Med. 2013. 274:67–76 https://www.ncbi.nlm.nih.gov/pubmed/23414424 23414424 | | | | X
463. | Sabia, S.,Elbaz, A.,Rouveau, N.,Brunner, E. J.,Kivimaki, M.,Singh-Manoux, A. Cumulative associations between midlife health behaviors and physical functioning in early old age: a 17-year prospective cohort study. J Am Geriatr Soc. 2014. 62:1860–8 https://www.ncbi.nlm.nih.gov/pubmed/25283337 25283337 | | X
464. | Sabrina, N.,Bai, C. H.,Chang, C. C.,Chien, Y. W.,Chen, J. R.,Chang, J. S. Serum Iron:Ferritin Ratio Predicts Healthy Body Composition and Reduced Risk of Severe Fatty Liver in Young Adult Women. Nutrients. 2017. 9:#pages# https://www.ncbi.nlm.nih.gov/pubmed/28777296 | X | | | X
465. | Saghafi-Asl, M.,Vaghef-Mehrabany, E. Comprehensive comparison of malnutrition and its associated factors between nursing home and community dwelling elderly: A case-control study from Northwestern Iran. Clin Nutr ESPEN. 2017. 21:51–58 https://www.ncbi.nlm.nih.gov/pubmed/30014869 30014869 | X | X
466. | Sallinen, J.,Pakarinen, A.,Ahtiainen, J.,Kraemer, W. J.,Volek, J. S.,Häkkinen, K. Relationship between diet and serum anabolic hormone responses to heavy-resistance exercise in men. International Journal of Sports Medicine. 2004. 25:627–633 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L39518142 10.1055/s-2004-815818 15532008 | | X | | X | | | | X
467. | Sallinen, J.,Pakarinen, A.,Fogelholm, M.,Alen, M.,Volek, J. S.,Kraemer, W. J., Hakkinen, K. Dietary intake, serum hormones, muscle mass and strength during strength training in 49 - 73-year-old men. Int J Sports Med. 2007. 28:1070–6 https://www.ncbi.nlm.nih.gov/pubmed/17497592 17497592 | | X | X
468. | Sallinen, J.,Pakarinen, A.,Fogelholm, M.,Sillanpaa, E.,Alen, M.,Volek, J. S., Kraemer, W. J.,Hakkinen, K. Serum basal hormone concentrations and muscle mass in aging women: effects of strength training and diet. Int J Sport Nutr Exerc Metab. 2006. 16:316–31 https://www.ncbi.nlm.nih.gov/pubmed/16948487 16948487 | | X
469. | Sammarco, R.,Marra, M.,Di Guglielmo, M. L.,Naccarato, M.,Contaldo, F., Poggiogalle, E.,Donini, L. M.,Pasanisi, F. Evaluation of Hypocaloric Diet With Protein Supplementation in Middle-Aged Sarcopenic Obese Women: A Pilot Study. Obes Facts. 2017. 10:160–167 https://www.ncbi.nlm.nih.gov/pubmed/28528340 28528340 | | X
470. | Sandoval-Insausti, H.,Perez-Tasigchana, R. F.,Lopez-Garcia, E.,Garcia-Esquinas, E.,Rodriguez-Artalejo, F.,Guallar-Castillon, P. Macronutrients Intake and Incident Frailty in Older Adults: A Prospective Cohort Study. J Gerontol A Biol Sci Med Sci. 2016. 71:1329–34 https://www.ncbi.nlm.nih.gov/pubmed/26946103 26946103 | | X | X
471. | Santillan-Diaz, C.,Ramirez-Sanchez, N.,Espinosa-Morales, R.,Orea-Tejeda, A., Llorente, L.,Rodriguez-Guevara, G.,Castillo-Martinez, L. Prevalence of rheumatoid cachexia assessed by bioelectrical impedance vector analysis and its relation with physical function. Clin Rheumatol. 2018. 37:607–614 https://www.ncbi.nlm.nih.gov/pubmed/29119481 29119481 | | X | | | | | | X
472. | Sarti, S.,Ruggiero, E.,Coin, A.,Toffanello, E. D.,Perissinotto, E.,Miotto, F.,Pintore, G.,Inelmen, E. M.,Manzato, E.,Sergi, G. Dietary intake and physical performance in healthy elderly women: a 3-year follow-up. Exp Gerontol. 2013. 48:250–4 https://www.ncbi.nlm.nih.gov/pubmed/23063988 23063988 | | X
473. | Sartor, F.,Jackson, M. J.,Squillace, C.,Shepherd, A.,Moore, J. P.,Ayer, D. E.,Kubis, H. P. Adaptive metabolic response to 4 weeks of sugar-sweetened beverage consumption in healthy, lightly active individuals and chronic high glucose availability in primary human myotubes. Eur J Nutr. 2013. 52:937–48 https://www.ncbi.nlm.nih.gov/pubmed/22733000 22733000 | X | X
474. | Sartorio, A.,Lafortuna, C. L.,Massarini, M.,Galvani, C. Effects of different training protocols on exercise performance during a short-term body weight reduction programme in severely obese patients. Eat Weight Disord. 2003. 8:36–43 https://www.ncbi.nlm.nih.gov/pubmed/12762623 12762623 | | X
475. | Sasaki, H.,Ishibashi, A.,Tsuchiya, Y.,Shimura, N.,Kurihara, T.,Ebi, K.,Goto, K. A 3-day high-fat/low-carbohydrate diet does not alter exercise-induced growth hormone response in healthy males. Growth Horm IGF Res. 2015. 25:304–11 https://www.ncbi.nlm.nih.gov/pubmed/26387476 26387476 | | X | | X
476. | Sawyer, J. C.,Wood, R. J.,Davidson, P. W.,Collins, S. M.,Matthews, T. D.,Gregory, S. M.,Paolone, V. J. Effects of a short-term carbohydrate-restricted diet on strength and power performance. J Strength Cond Res. 2013. 27:2255–62 https://www.ncbi.nlm.nih.gov/pubmed/23774282 23774282 | | | | | | | | X
477. | Sawyer, J. C.,Wood, R. J.,Davidson, P. W.,Collins, S. M.,Matthews, T. D.,Gregory, S. M.,Paolone, V. J. Effects of a short-term carbohydrate restricted diet on strength and power performance. #journal#. 2013. 27:2255–2262 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L1369877351 10.1519/JSC.0b013e31827da314 | X | | | | | | | X
478. | Schacht, S. R.,Lind, M. V.,Mertz, K. H.,Bulow, J.,Bechshoft, R.,Hojfeldt, G.,Schucany, A.,Hjulmand, M.,Sidoli, C.,Andersen, S. B.,Jensen, M.,Reitelseder, S., Holm, L.,Tetens, I. Development of a Mobility Diet Score (MDS) and Associations With Bone Mineral Density and Muscle Function in Older Adults. Front Nutr. 2019. 6:114 https://www.ncbi.nlm.nih.gov/pubmed/31552255 31552255 | | | | X
479. | Schilling, B. K.,Stone, M. H.,Utter, A.,Kearney, J. T.,Johnson, M.,Coglianese, R., Smith, L.,O’Bryant, H. S.,Fry, A. C.,Starks, M.,Keith, R.,Stone, M. E. Creatine supplementation and health variables: a retrospective study. Med Sci Sports Exerc. 2001. 33:183–8 https://www.ncbi.nlm.nih.gov/pubmed/11224803 11224803 | | X | | | | | | X
480. | Schilp, J.,Kruizenga, H. M.,Wijnhoven, H. A.,van Binsbergen, J. J.,Visser, M. Effects of a dietetic treatment in older, undernourished, community-dwelling individuals in primary care: a randomized controlled trial. European journal of nutrition. 2013. 52:1939–1948 https://www.cochranelibrary.com/central/doi/10.1002/central/CN-00961710/full 23361389 | | X
481. | Schmid, A.,Weiss, M.,Heseker, H. Recording the nutrient intake of nursing home residents by food weighing method and measuring the physical activity. J Nutr Health Aging. 2003. 7:294–5 https://www.ncbi.nlm.nih.gov/pubmed/12917742 12917742 | X | X
482. | Schonenberger, K. A.,Reber, E.,Bally, L.,Geiser, T.,Lin, D.,Stanga, Z. Nutritional assessment in adults with cystic fibrosis. Nutrition. 2019. 67-68:110518 https://www.ncbi.nlm.nih.gov/pubmed/31473521 31473521 | | | | | | | | X
483. | Schrager, M. A.,Hilton, J.,Gould, R.,Kelly, V. E. Effects of blueberry supplementation on measures of functional mobility in older adults. Appl Physiol Nutr Metab. 2015. 40:543–9 https://www.ncbi.nlm.nih.gov/pubmed/25909473 25909473 | | X
484. | Schrijvers, J. K.,McNaughton, S. A.,Beck, K. L.,Kruger, R. Exploring the Dietary Patterns of Young New Zealand Women and Associations with BMI and Body Fat. Nutrients. 2016. 8:#pages# https://www.ncbi.nlm.nih.gov/pubmed/27472358 | X | | | X
485. | Schumacher, A.,Peersen, K.,Sommervoll, L.,Seljeflot, I.,Arnesen, H.,Otterstad, J. E. Physical performance is associated with markers of vascular inflammation in patients with coronary heart disease. Eur J Cardiovasc Prev Rehabil. 2006. 13:356–62 https://www.ncbi.nlm.nih.gov/pubmed/16926664 16926664 | | X | | X | | | | X
486. | Scott, D.,Blizzard, L.,Fell, J.,Giles, G.,Jones, G. Associations between dietary nutrient intake and muscle mass and strength in community-dwelling older adults: the Tasmanian Older Adult Cohort Study. J Am Geriatr Soc. 2010. 58:2129–34 https://www.ncbi.nlm.nih.gov/pubmed/21054294 21054294 | | X
487. | Seino, S.,Sumi, K.,Narita, M.,Yokoyama, Y.,Ashida, K.,Kitamura, A.,Shinkai, S. Effects of Low-Dose Dairy Protein Plus Micronutrient Supplementation during Resistance Exercise on Muscle Mass and Physical Performance in Older Adults: a Randomized, Controlled Trial. Journal of nutrition, health & aging. 2018. 22:59–67 https://www.cochranelibrary.com/central/doi/10.1002/central/CN-01340380/full | | X
488. | Semba, R. D.,Gonzalez-Freire, M.,Tanaka, T.,Biancotto, A.,Zhang, P.,Shardell, M.,Moaddel, R.,Ferrucci, L. Elevated Plasma Growth and Differentiation Factor-15 is Associated with Slower Gait Speed and Lower Physical Performance in Healthy Community-Dwelling Adults. J Gerontol A Biol Sci Med Sci. 2019. #volume#:#pages# https://www.ncbi.nlm.nih.gov/pubmed/30874790 | | X
489. | Seo, M. H.,Kim, M. K.,Park, S. E.,Rhee, E. J.,Park, C. Y.,Lee, W. Y.,Baek, K. H., Song, K. H.,Kang, M. I.,Oh, K. W. The association between daily calcium intake and sarcopenia in older, non-obese Korean adults: the fourth Korea National Health and Nutrition Examination Survey (KNHANES IV) 2009. Endocr J. 2013. 60:679–86 https://www.ncbi.nlm.nih.gov/pubmed/23357977 23357977 | X
490. | Shahar, D. R.,Houston, D. K.,Hue, T. F.,Lee, J. S.,Sahyoun, N. R.,Tylavsky, F. A., Geva, D.,Vardi, H.,Harris, T. B. Adherence to mediterranean diet and decline in walking speed over 8 years in community-dwelling older adults. J Am Geriatr Soc. 2012. 60:1881–8 https://www.ncbi.nlm.nih.gov/pubmed/23035758 23035758 | | | | X
491. | Shahar, S.,Vanoh, D.,Mat Ludin, A. F.,Singh, D. K. A.,Hamid, T. A. Factors associated with poor socioeconomic status among Malaysian older adults: an analysis according to urban and rural settings. BMC Public Health. 2019. 19:549 https://www.ncbi.nlm.nih.gov/pubmed/31196023 31196023 | | X | | X
492. | Sharkey, J. R. Diet and health outcomes in vulnerable populations. Ann N Y Acad Sci. 2008. 1136:210–7 https://www.ncbi.nlm.nih.gov/pubmed/18579883 18579883 | X
493. | Sharkey, J. R.,Branch, L. G. Gender difference in physical performance, body composition and dietary intake in homebound elders. J Women Aging. 2004. 16:71–90 https://www.ncbi.nlm.nih.gov/pubmed/15778170 | X | X
494. | Sharkey, J. R.,Branch, L. G.,Giuliani, C.,Zohoori, M.,Haines, P. S. Nutrient intake and BMI as predictors of severity of ADL disability over 1 year in homebound elders. J Nutr Health Aging. 2004. 8:131–9 https://www.ncbi.nlm.nih.gov/pubmed/15129297 15129297 | | X
495. | Sharkey, J. R.,Giuliani, C.,Haines, P. S.,Branch, L. G.,Busby-Whitehead, J., Zohoori, N. Summary measure of dietary musculoskeletal nutrient (calcium, vitamin D, magnesium, and phosphorus) intakes is associated with lower-extremity physical performance in homebound elderly men and women. Am J Clin Nutr. 2003. 77:847–56 https://www.ncbi.nlm.nih.gov/pubmed/12663282 12663282 | X | X
496. | Shatenstein, B.,Gauvin, L.,Keller, H.,Richard, L.,Gaudreau, P.,Giroux, F.,Jabbour, M.,Morais, J. A.,Payette, H. Individual and collective factors predicting change in diet quality over 3 years in a subset of older men and women from the NuAge cohort. Eur J Nutr. 2016. 55:1671–81 https://www.ncbi.nlm.nih.gov/pubmed/26169872 26169872 | | | | X
497. | Shaw, S. C.,Parsons, C. M.,Fuggle, N. R.,Edwards, M. H.,Robinson, S. M., Dennison, E. M.,Cooper, C.,Ward, K. A. Diet Quality and Bone Measurements Using HRpQCT and pQCT in Older Community-Dwelling Adults from the Hertfordshire Cohort Study. Calcified Tissue International. 2018. 103:494–500 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L622665736 10.1007/s00223-018-0445-x 29931462 | | | | X
498. | Shea, M. K.,Loeser, R. F.,McAlindon, T. E.,Houston, D. K.,Kritchevsky, S. B.,Booth, S. L. Association of Vitamin K Status Combined With Vitamin D Status and Lower-Extremity Function: A Prospective Analysis of Two Knee Osteoarthritis Cohorts. Arthritis Care Res (Hoboken). 2018. 70:1150–1159 https://www.ncbi.nlm.nih.gov/pubmed/29045002 29045002 | | X
499. | Shea, M.,Loeser, R. F.,Kritchevsky, S. B.,Houston, D. K.,McAlindon, T. E.,Booth, S. L. Is there a synergistic role for vitamin K and vitamin D in lower extremity function related to knee osteoarthritis? The osteoarthritis initiative and health, aging and body composition studies. Osteoarthritis and cartilage. Conference: 2017 osteoarthritis research society international, OARSI world congress. United states. 2017. 25:S185–S186 https://www.cochranelibrary.com/central/doi/10.1002/central/CN-01470379/full | | X
500. | Sheu, W. H. H.,Lee, W. J.,Chang, R. L.,Chen, Y. T. Plasma tumor necrosis factor alpha levels and insulin sensitivity in hypertensive subjects. Clin Exp Hypertens. 2000. 22:595–606 https://www.ncbi.nlm.nih.gov/pubmed/10972164 10972164 | | X | | X
501. | Shiina, Y.,Matsumoto, N.,Okamura, D.,Takahashi, Y.,Kijima, Y.,Fukuda, T., Kawamatsu, N.,Nishihata, Y.,Komiyama, N.,Niwa, K. Sarcopenia in adults with congenital heart disease: Nutritional status, dietary intake, and resistance training. J Cardiol. 2019. 74:84–89 https://www.ncbi.nlm.nih.gov/pubmed/30713126 30713126 | | | | | | | | X
502. | Shimoda, T.,Suzuki, T.,Takahashi, N.,Tsutsumi, K.,Samukawa, M.,Yoshimachi, S.,Goto, T.,Enomoto, H.,Kise, N.,Ogasawara, K.,Yoshimura, S. Nutritional Status and Body Composition of Independently Living Older Adults in a Snowy Region of Japan. Gerontol Geriatr Med. 2017. 3:2333721417706854 https://www.ncbi.nlm.nih.gov/pubmed/28516130 28516130 | X
503. | Shumilov, D.,Heymsfield, S. B.,Redman, L. M.,Smith, S. R.,Bray, G. A.,Kalluri, K., Dey, J. New compartment model analysis of lean-mass and fat-mass growth with overfeeding. Nutrition. 2016. 32:590–600 https://www.ncbi.nlm.nih.gov/pubmed/26740258 26740258 | X | | | | | | | X
504. | Singh, N.,Graves, J.,Taylor, P. D.,MacAllister, R. J.,Singer, D. R. Effects of a ‘healthy’ diet and of acute and long-term vitamin C on vascular function in healthy older subjects. Cardiovasc Res. 2002. 56:118–25 https://www.ncbi.nlm.nih.gov/pubmed/12237172 12237172 | | | | X
505. | Smee, D. J.,Pumpa, K.,Falchi, M.,Lithander, F. E. The relationship between diet quality and falls risk, physical function and body composition in older adults. Journal of Nutrition, Health and Aging. 2015. 19:1037–1042 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L607582380 10.1007/s12603-015-0666-x | X
506. | Smith, A.,Gray, J. Considering the benefits of egg consumption for older people at risk of sarcopenia. Br J Community Nurs. 2016. 21:305–9 https://www.ncbi.nlm.nih.gov/pubmed/27270199 27270199 | X
507. | Smith, G. I.,Yoshino, J.,Kelly, S. C.,Reeds, D. N.,Okunade, A.,Patterson, B. W., Klein, S.,Mittendorfer, B. High-Protein Intake during Weight Loss Therapy Eliminates the Weight-Loss-Induced Improvement in Insulin Action in Obese Postmenopausal Women. Cell Rep. 2016. 17:849–861 https://www.ncbi.nlm.nih.gov/pubmed/27732859 27732859 | | | | X
508. | Smoliner, C.,Norman, K.,Scheufele, R.,Hartig, W.,Pirlich, M.,Lochs, H. Effects of food fortification on nutritional and functional status in frail elderly nursing home residents at risk of malnutrition. Nutrition (burbank, los angeles county, calif.). 2008. 24:1139–1144 https://www.cochranelibrary.com/central/doi/10.1002/central/CN-00665676/full | | X
509. | Snijders, T.,Verdijk, L. B.,McKay, B. R.,Smeets, J. S.,van Kranenburg, J.,Groen, B. B.,Parise, G.,Greenhaff, P.,van Loon, L. J. Acute dietary protein intake restriction is associated with changes in myostatin expression after a single bout of resistance exercise in healthy young men. J Nutr. 2014. 144:137–45 https://www.ncbi.nlm.nih.gov/pubmed/24306214 24306214 | | | | X
510. | Son, J. W.,Lee, S. S.,Kim, S. R.,Yoo, S. J.,Cha, B. Y.,Son, H. Y.,Cho, N. H. Low muscle mass and risk of type 2 diabetes in middle-aged and older adults: findings from the KoGES. Diabetologia. 2017. 60:865–872 https://www.ncbi.nlm.nih.gov/pubmed/28102434 28102434 | | X
511. | Song, M. Y.,Ruts, E.,Kim, J.,Janumala, I.,Heymsfield, S.,Gallagher, D. Sarcopenia and increased adipose tissue infiltration of muscle in elderly African American women. Am J Clin Nutr. 2004. 79:874–80 https://www.ncbi.nlm.nih.gov/pubmed/15113728 15113728 | | X
512. | Stathakos, D.,Pratsinis, H.,Zachos, I.,Vlahaki, I.,Gianakopoulou, A.,Zianni, D., Kletsas, D. Greek centenarians: assessment of functional health status and life-style characteristics. Exp Gerontol. 2005. 40:512–8 https://www.ncbi.nlm.nih.gov/pubmed/15935588 15935588 | X | | | X
513. | Stefler, D.,Hu, Y.,Malyutina, S.,Pajak, A.,Kubinova, R.,Peasey, A.,Pikhart, H., Rodriguez-Artalejo, F.,Bobak, M. Mediterranean diet and physical functioning trajectories in Eastern Europe: Findings from the HAPIEE study. PLoS ONE. 2018. 13:#pages# http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L622981445 10.1371/journal.pone.0200460 | | | | X
514. | Stookey, J. D.,Adair, L. S.,Popkin, B. M. Do protein and energy intakes explain long-term changes in body composition?. J Nutr Health Aging. 2005. 9:5–17 https://www.ncbi.nlm.nih.gov/pubmed/15750660 15750660 | | X | | X | | | X
515. | Stookey, J. D.,Adair, L.,Stevens, J.,Popkin, B. M. Patterns of long-term change in body composition are associated with diet, activity, income and urban residence among older adults in China. J Nutr. 2001. 131:2433s–40s https://www.ncbi.nlm.nih.gov/pubmed/11533290 11533290 | | X | | X
516. | Stow, R.,Ives, N.,Smith, C.,Rick, C.,Rushton, A. A cluster randomised feasibility trial evaluating nutritional interventions in the treatment of malnutrition in care home adult residents. Trials. 2015. 16:433 https://www.ncbi.nlm.nih.gov/pubmed/26416253 26416253 | | X
517. | Straight, C. R.,Dorfman, L. R.,Cottell, K. E.,Krol, J. M.,Lofgren, I. E.,Delmonico, M. J. Effects of resistance training and dietary changes on physical function and body composition in overweight and obese older adults. J Phys Act Health. 2012. 9:875–83 https://www.ncbi.nlm.nih.gov/pubmed/21952180 21952180 | X | X
518. | Strandberg, E.,Edholm, P.,Ponsot, E.,Wahlin-Larsson, B.,Hellmen, E.,Nilsson, A., Engfeldt, P.,Cederholm, T.,Riserus, U.,Kadi, F. Influence of combined resistance training and healthy diet on muscle mass in healthy elderly women: a randomized controlled trial. J Appl Physiol (1985). 2015. 119:918–25 https://www.ncbi.nlm.nih.gov/pubmed/26338453 26338453 | | X
519. | Strandberg, E.,Ponsot, E.,Piehl-Aulin, K.,Falk, G.,Kadi, F. Resistance Training Alone or Combined With N-3 PUFA-Rich Diet in Older Women: Effects on Muscle Fiber Hypertrophy. The journals of gerontology. Series A, Biological sciences and medical sciences. 2019. 74:489–494 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L626804282 10.1093/gerona/gly130 | | X
520. | Straznicky, N. E.,Eikelis, N.,Nestel, P. J.,Dixon, J. B.,Dawood, T.,Grima, M. T.,Sari, C. I.,Schlaich, M. P.,Esler, M. D.,Tilbrook, A. J.,Lambert, G. W.,Lambert, E. A. Baseline sympathetic nervous system activity predicts dietary weight loss in obese metabolic syndrome subjects. J Clin Endocrinol Metab. 2012. 97:605–13 https://www.ncbi.nlm.nih.gov/pubmed/22090279 22090279 | | X | | X
521. | Struijk, E. A.,Guallar-Castillon, P.,Rodriguez-Artalejo, F.,Lopez-Garcia, E. Mediterranean Dietary Patterns and Impaired Physical Function in Older Adults. J Gerontol A Biol Sci Med Sci. 2018. 73:333–339 https://www.ncbi.nlm.nih.gov/pubmed/28329809 28329809 | | | | X
522. | Sturgeon, K. M.,Dean, L. T.,Heroux, M.,Kane, J.,Bauer, T.,Palmer, E.,Long, J., Lynch, S.,Jacobs, L.,Sarwer, D. B.,Leonard, M. B.,Schmitz, K. Commercially available lifestyle modification program: randomized controlled trial addressing heart and bone health in BRCA1/2+ breast cancer survivors after risk-reducing salpingo-oophorectomy. J Cancer Surviv. 2017. 11:246–255 https://www.ncbi.nlm.nih.gov/pubmed/27873046 27873046 | | X | | | | | | X
523. | Sugihara Junior, P.,Ribeiro, A. S.,Nabuco, H. C. G.,Fernandes, R. R.,Tomeleri, C. M.,Cunha, P. M.,Venturini, D.,Barbosa, D. S.,Schoenfeld, B. J.,Cyrino, E. S. Effects of Whey Protein Supplementation Associated With Resistance Training on Muscular Strength, Hypertrophy, and Muscle Quality in Preconditioned Older Women. Int J Sport Nutr Exerc Metab. 2018. 28:528–535 https://www.ncbi.nlm.nih.gov/pubmed/29252039 29252039 | | X
524. | Suh, Y.,Kang, H.,Kim, M.,Kim, S. Effect of weight reduction on Korean high protein diet in obese women. Obesity reviews. 2014. 15:229 https://www.cochranelibrary.com/central/doi/10.1002/central/CN-01041831/full | X | | | | X
525. | Tai, K.,Visvanathan, R.,Hammond, A. J.,Wishart, J. M.,Horowitz, M.,Chapman, I. M. Fasting ghrelin is related to skeletal muscle mass in healthy adults. Eur J Nutr. 2009. 48:176–83 https://www.ncbi.nlm.nih.gov/pubmed/19198916 19198916 | X | X
526. | Talegawkar, S. A.,Bandinelli, S.,Bandeen-Roche, K.,Chen, P.,Milaneschi, Y.,Tanaka, T.,Semba, R. D.,Guralnik, J. M.,Ferrucci, L. A higher adherence to a Mediterranean-style diet is inversely associated with the development of frailty in community-dwelling elderly men and women. J Nutr. 2012. 142:2161–6 https://www.ncbi.nlm.nih.gov/pubmed/23096005 23096005 | | | | X
527. | Ten Haaf, D. S. M. T.,De Regt, M. F.,Visser, M.,Witteman, B. J. M.,De Vries, J. H. M.,Eijsvogels, T. M. H.,Hopman, M. T. E. Insufficient protein intake is highly prevalent among physically active elderly. Journal of Nutrition, Health and Aging. 2018. 22:1112–1114 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L626914117 10.1007/s12603-018-1075-8 | X
528. | Ten Haaf, D. S. M.,Eijsvogels, T. M. H.,Bongers, Ccwg,Horstman, A. M. H.,Timmers, S.,de Groot, Lcpgm,Hopman, M. T. E. Protein supplementation improves lean body mass in physically active older adults: a randomized placebo-controlled trial. J Cachexia Sarcopenia Muscle. 2019. 10:298–310 https://www.ncbi.nlm.nih.gov/pubmed/30848096 30848096 | | X
529. | Tepper, S.,Alter Sivashensky, A.,Rivkah Shahar, D.,Geva, D.,Cukierman-Yaffe, T. The Association between Mediterranean Diet and the Risk of Falls and Physical Function Indices in Older Type 2 Diabetic People Varies by Age. Nutrients. 2018. 10:#pages# https://www.ncbi.nlm.nih.gov/pubmed/29899221 | X
530. | Ter Borg, S.,de Groot, L. C.,Mijnarends, D. M.,de Vries, J. H.,Verlaan, S.,Meijboom, S.,Luiking, Y. C.,Schols, J. M. Differences in Nutrient Intake and Biochemical Nutrient Status Between Sarcopenic and Nonsarcopenic Older Adults-Results From the Maastricht Sarcopenia Study. J Am Med Dir Assoc. 2016. 17:393–401 https://www.ncbi.nlm.nih.gov/pubmed/26825685 26825685 | X
531. | Terp, R.,Jacobsen, K. O.,Kannegaard, P.,Larsen, A. M.,Madsen, O. R.,Noiesen, E. A multidisciplinary nutritional intervention program across sectors improved the nutritional status and self-rated health in geriatric patients at nutritional risk-a randomized controlled trial. Clinical nutrition (edinburgh, scotland). 2016. 35:S55- https://www.cochranelibrary.com/central/doi/10.1002/central/CN-01361499/full | | | | | X
532. | Thalacker-Mercer, A. E.,Fleet, J. C.,Craig, B. A.,Campbell, W. W. The skeletal muscle transcript profile reflects accommodative responses to inadequate protein intake in younger and older males. J Nutr Biochem. 2010. 21:1076–82 https://www.ncbi.nlm.nih.gov/pubmed/20149619 20149619 | | | | X
533. | Thalacker-Mercer, A. E.,Petrella, J. K.,Bamman, M. M. Does habitual dietary intake influence myofiber hypertrophy in response to resistance training? A cluster analysis. Appl Physiol Nutr Metab. 2009. 34:632–9 https://www.ncbi.nlm.nih.gov/pubmed/19767798 19767798 | | X | | X
534. | Thompson, B. J.,Ryan, E. D.,Sobolewski, E. J.,Smith-Ryan, A. E. Dietary protein intake is associated with maximal and explosive strength of the leg flexors in young and older blue collar workers. Nutr Res. 2015. 35:280–6 https://www.ncbi.nlm.nih.gov/pubmed/25753919 25753919 | X
535. | Tieland, M.,Borgonjen-Van den Berg, K. J.,Van Loon, L. J.,de Groot, L. C. Dietary Protein Intake in Dutch Elderly People: A Focus on Protein Sources. Nutrients. 2015. 7:9697–706 https://www.ncbi.nlm.nih.gov/pubmed/26610565 26610565 | X | | | X
536. | Tieland, M.,Borgonjen-Van den Berg, K. J.,van Loon, L. J.,de Groot, L. C. Dietary protein intake in community-dwelling, frail, and institutionalized elderly people: scope for improvement. Eur J Nutr. 2012. 51:173–9 https://www.ncbi.nlm.nih.gov/pubmed/21562887 21562887 | X | X | | X
537. | Tieland, M.,van de Rest, O.,Dirks, M. L.,van der Zwaluw, N.,Mensink, M.,van Loon, L. J.,de Groot, L. C. Protein supplementation improves physical performance in frail elderly people: a randomized, double-blind, placebo-controlled trial. J Am Med Dir Assoc. 2012. 13:720–6 https://www.ncbi.nlm.nih.gov/pubmed/22889730 22889730 | | X | | X
538. | Tieland, M.,Van De Rest, O.,Verdijk, L.,De Groot, L.,Van Loon, L. The effects of protein supplementation during prolonged resistance type exercise training on muscle mass and function in frail elderly. Clinical nutrition, supplement.. 2011. 6:111 https://www.cochranelibrary.com/central/doi/10.1002/central/CN-01034622/full | | | | | X
539. | Tomey, K. M.,Sowers, M. R.,Crandall, C.,Johnston, J.,Jannausch, M.,Yosef, M. Dietary intake related to prevalent functional limitations in midlife women. Am J Epidemiol. 2008. 167:935–43 https://www.ncbi.nlm.nih.gov/pubmed/18250080 18250080 | | | | X
540. | Tomlinson, D. J.,Erskine, R. M.,Morse, C. I.,Onambele, G. L. Body Fat Percentage, Body Mass Index, Fat Mass Index and the Ageing Bone: Their Singular and Combined Roles Linked to Physical Activity and Diet. Nutrients. 2019. 11:#pages# https://www.ncbi.nlm.nih.gov/pubmed/30669348 | X | | | X
541. | Tomlinson, D. J.,Erskine, R. M.,Morse, C. I.,Onambele, G. L. Impact of Above-Average Proanabolic Nutrients Is Overridden by High Protein and Energy Intake in the Muscle-Tendon Unit Characteristics of Middle- to Older-Aged Adults. J Nutr. 2018. 148:1776–1785 https://www.ncbi.nlm.nih.gov/pubmed/30247586 30247586 | X
542. | Torres, S. J.,Robinson, S.,Orellana, L.,O’Connell, S. L.,Grimes, C. A.,Mundell, N. L.,Dunstan, D. W.,Nowson, C. A.,Daly, R. M. Effects of progressive resistance training combined with a protein-enriched lean red meat diet on health-related quality of life in elderly women: secondary analysis of a 4-month cluster randomised controlled trial. Br J Nutr. 2017. 117:1550–1559 https://www.ncbi.nlm.nih.gov/pubmed/28721837 28721837 | | X | | X
543. | Trajanoska, K.,Schoufour, J. D.,Darweesh, S. K.,Benz, E.,Medina-Gomez, C., Alferink, L. J.,Lahousse, L.,Brusselle, G.,Stricker, B.,Darwish Murad, S.,Zillikens, M. C.,Uitterlinden, A. G.,Ikram, M. A.,Franco, O. H.,Rivadeneira, F. Sarcopenia and Its Clinical Correlates in the General Population: The Rotterdam Study. J Bone Miner Res. 2018. 33:1209–1218 https://www.ncbi.nlm.nih.gov/pubmed/29502340 29502340 | X
544. | Trappe, S.,Creer, A.,Slivka, D.,Minchev, K.,Trappe, T. Single muscle fiber function with concurrent exercise or nutrition countermeasures during 60 days of bed rest in women. J Appl Physiol (1985). 2007. 103:1242–50 https://www.ncbi.nlm.nih.gov/pubmed/17641219 17641219 | | X | | | | | | X
545. | Trappe, T. A.,Burd, N. A.,Louis, E. S.,Lee, G. A.,Trappe, S. W. Influence of concurrent exercise or nutrition countermeasures on thigh and calf muscle size and function during 60 days of bed rest in women. Acta Physiol (Oxf). 2007. 191:147–59 https://www.ncbi.nlm.nih.gov/pubmed/17655736 17655736 | | X | | | | | | X
546. | Trejo, A.,Tarrats, R. M.,Alonso, M. E.,Boll, M. C.,Ochoa, A.,Velasquez, L. Assessment of the nutrition status of patients with Huntington’s disease. Nutrition. 2004. 20:192–6 https://www.ncbi.nlm.nih.gov/pubmed/14962685 14962685 | | X | | X | | | | X
547. | Trevisan, C.,Veronese, N.,Maggi, S.,Baggio, G.,Toffanello, E. D.,Zambon, S., Sartori, L.,Musacchio, E.,Perissinotto, E.,Crepaldi, G.,Manzato, E.,Sergi, G. Factors Influencing Transitions Between Frailty States in Elderly Adults: The Progetto Veneto Anziani Longitudinal Study. Journal of the American Geriatrics Society. 2017. 65:179–184 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L613714272 10.1111/jgs.14515 27861714 | | X
548. | Treyzon, L.,Chen, S.,Hong, K.,Yan, E.,Carpenter, C. L.,Thames, G.,Bowerman, S., Wang, H. J.,Elashoff, R.,Li, Z. A controlled trial of protein enrichment of meal replacements for weight reduction with retention of lean body mass. Nutr J. 2008. 7:23 https://www.ncbi.nlm.nih.gov/pubmed/18752682 18752682 | | X | | X
549. | Trierweiler, H.,Kisielewicz, G.,Hoffmann Jonasson, T.,Rasmussen Petterle, R., Aguiar Moreira, C.,Zeghbi Cochenski Borba, V. Sarcopenia: a chronic complication of type 2 diabetes mellitus. Diabetol Metab Syndr. 2018. 10:25 https://www.ncbi.nlm.nih.gov/pubmed/29632617 29632617 | X
550. | Tylner, S.,Cederholm, T.,Faxen-Irving, G. Effects on Weight, Blood Lipids, Serum Fatty Acid Profile and Coagulation by an Energy-Dense Formula to Older Care Residents: A Randomized Controlled Crossover Trial. J Am Med Dir Assoc. 2016. 17:275.e5–11 https://www.ncbi.nlm.nih.gov/pubmed/26810442 | | X
551. | Tyrovolas, S.,Bountziouka, V.,Papairakleous, N.,Zeimbekis, A.,Anastassiou, F., Gotsis, E.,Metallinos, G.,Polychronopoulos, E.,Lionis, C.,Panagiotakos, D. Adherence to the Mediterranean diet is associated with lower prevalence of obesity among elderly people living in Mediterranean islands: the MEDIS study. Int J Food Sci Nutr. 2009. 60 Suppl 6:137–50 https://www.ncbi.nlm.nih.gov/pubmed/19672745 19672745 | | | | X
552. | Tyrovolas, S.,Haro, J. M.,Mariolis, A.,Piscopo, S.,Valacchi, G.,Bountziouka, V.,Anastasiou, F.,Zeimbekis, A.,Tyrovola, D.,Foscolou, A.,Gotsis, E.,Metallinos, G., Tur, J. A.,Matalas, A.,Lionis, C.,Polychronopoulos, E.,Panagiotakos, D. Skeletal muscle mass and body fat in relation to successful ageing of older adults: The multi-national MEDIS study. Arch Gerontol Geriatr. 2016. 66:95–101 https://www.ncbi.nlm.nih.gov/pubmed/27266673 27266673 | X | X | | X
553. | Urbain, P.,Strom, L.,Morawski, L.,Wehrle, A.,Deibert, P.,Bertz, H. Impact of a 6-week non-energy-restricted ketogenic diet on physical fitness, body composition and biochemical parameters in healthy adults. Nutr Metab (Lond). 2017. 14:17 https://www.ncbi.nlm.nih.gov/pubmed/28239404 28239404 | X
554. | Uritani, D.,Matsumoto, D.,Asano, Y.,Yoshizaki, K.,Nishida, Y.,Shima, M. Effects of regular exercise and nutritional guidance on body composition, blood pressure, muscle strength and health-related quality of life in community-dwelling Japanese women. Obes Res Clin Pract. 2013. 7:e155–e163 https://www.ncbi.nlm.nih.gov/pubmed/24331777 24331777 | | X
555. | van Dongen, E. J. I.,Haveman-Nies, A.,Wezenbeek, N. L. W.,Dorhout, B. G.,Doets, E. L.,de Groot, Lcpgm Effect, process, and economic evaluation of a combined resistance exercise and diet intervention (ProMuscle in Practice) for community-dwelling older adults: design and methods of a randomised controlled trial. BMC Public Health. 2018. 18:877 https://www.ncbi.nlm.nih.gov/pubmed/30005654 30005654 | X | X
556. | Van Proeyen, K.,Szlufcik, K.,Nielens, H.,Deldicque, L.,Van Dyck, R.,Ramaekers, M.,Hespel, P. High-fat diet overrules the effects of training on fiber-specific intramyocellular lipid utilization during exercise. J Appl Physiol (1985). 2011. 111:108–16 https://www.ncbi.nlm.nih.gov/pubmed/21551007 21551007 | | X | | X
557. | Van Wymelbeke, V.,Brondel, L.,Bon, F.,Martin-Pfitzenmeyer, I.,Manckoundia, P. An innovative brioche enriched in protein and energy improves the nutritional status of malnourished nursing home residents compared to oral nutritional supplement and usual breakfast: FARINE+ project. Clin Nutr ESPEN. 2016. 15:93–100 https://www.ncbi.nlm.nih.gov/pubmed/28531791 28531791 | | X
558. | Van Zant, R. S.,Conway, J. M.,Seale, J. L. A moderate carbohydrate and fat diet does not impair strength performance in moderately trained males. Journal of Sports Medicine and Physical Fitness. 2002. 42:31–37 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L34285877 | | X | | | | | | X
559. | Vanacore, D.,Messina, G.,Lama, S.,Bitti, G.,Ambrosio, P.,Tenore, G.,Messina, A., Monda, V.,Zappavigna, S.,Boccellino, M.,Novellino, E.,Monda, M.,Stiuso, P. Effect of restriction vegan diet’s on muscle mass, oxidative status, and myocytes differentiation: A pilot study. J Cell Physiol. 2018. 233:9345–9353 https://www.ncbi.nlm.nih.gov/pubmed/29319158 29319158 | X | X | | X
560. | Vargas, S.,Romance, R.,Petro, J. L.,Bonilla, D. A.,Galancho, I.,Espinar, S.,Kreider, R. B.,Benitez-Porres, J. Efficacy of ketogenic diet on body composition during resistance training in trained men: a randomized controlled trial. J Int Soc Sports Nutr. 2018. 15:31 https://www.ncbi.nlm.nih.gov/pubmed/29986720 29986720 | | X | X
561. | Velho, S.,Moco, S.,Ferreira, A.,Cruz, R.,Agostinho, L.,Cabral, M. S.,Luz, G.,Lopes, F.,Teixeira, J. A.,Strecht, J.,Coelho, J. L. P.,Maio, R.,Cravo, M.,Baracos, V. E. Dietary patterns and their relationships to sarcopenia in Portuguese patients with gastrointestinal cancer: An exploratory study. Nutrition. 2019. 63-64:193–199 https://www.ncbi.nlm.nih.gov/pubmed/31029047 31029047 | | | | | | | | X
562. | Vercambre, M. N.,Boutron-Ruault, M. C.,Ritchie, K.,Clavel-Chapelon, F.,Berr, C. Long-term association of food and nutrient intakes with cognitive and functional decline: a 13-year follow-up study of elderly French women. Br J Nutr. 2009. 102:419–27 https://www.ncbi.nlm.nih.gov/pubmed/19203415 19203415 | | | | X
563. | Verhoeven, S.,Vanschoonbeek, K.,Verdijk, L. B.,Koopman, R.,Wodzig, W. K., Dendale, P.,van Loon, L. J. Long-term leucine supplementation does not increase muscle mass or strength in healthy elderly men. Am J Clin Nutr. 2009. 89:1468–75 https://www.ncbi.nlm.nih.gov/pubmed/19321567 19321567 | | X
564. | Verlaan, S.,Aspray, T. J.,Bauer, J. M.,Cederholm, T.,Hemsworth, J.,Hill, T. R.,McPhee, J. S.,Piasecki, M.,Seal, C.,Sieber, C. C.,Ter Borg, S.,Wijers, S. L.,Brandt, K. Nutritional status, body composition, and quality of life in community-dwelling sarcopenic and non-sarcopenic older adults: A case-control study. Clin Nutr. 2017. 36:267–274 https://www.ncbi.nlm.nih.gov/pubmed/26689868 26689868 | X
565. | Verlaan, S.,Maier, A. B.,Bauer, J. M.,Bautmans, I.,Brandt, K.,Donini, L. M.,Maggio, M.,McMurdo, M. E. T.,Mets, T.,Seal, C.,Wijers, S. L. J.,Sieber, C.,Boirie, Y., Cederholm, T. Sufficient levels of 25-hydroxyvitamin D and protein intake required to increase muscle mass in sarcopenic older adults - The PROVIDE study. Clin Nutr. 2018. 37:551–557 https://www.ncbi.nlm.nih.gov/pubmed/28132725 28132725 | | | | | | | | X
566. | Veronese, N.,Stubbs, B.,Maggi, S.,Notarnicola, M.,Barbagallo, M.,Firth, J., Dominguez, L. J.,Caruso, M. G. Dietary Magnesium and Incident Frailty in Older People at Risk for Knee Osteoarthritis: An Eight-Year Longitudinal Study. Nutrients. 2017. 9:#pages# https://www.ncbi.nlm.nih.gov/pubmed/29144404 | | X
567. | Verreijen, A. M.,Engberink, M. F.,Houston, D. K.,Brouwer, I. A.,Cawthon, P. M., Newman, A. B.,Tylavsky, F. A.,Harris, T. B.,Weijs, P. J. M.,Visser, M. Dietary protein intake is not associated with 5-y change in mid-thigh muscle cross-sectional area by computed tomography in older adults: the Health, Aging, and Body Composition (Health ABC) Study. Am J Clin Nutr. 2019. 109:535–543 https://www.ncbi.nlm.nih.gov/pubmed/30850837 30850837 | | X
568. | Verreijen, A. M.,Engberink, M. F.,Memelink, R. G.,van der Plas, S. E.,Visser, M., Weijs, P. J. Effect of a high protein diet and/or resistance exercise on the preservation of fat free mass during weight loss in overweight and obese older adults: a randomized controlled trial. Nutr J. 2017. 16:10 https://www.ncbi.nlm.nih.gov/pubmed/28166780 28166780 | | | | X
569. | Verreijen, A. M.,Engberink, M. F.,Memelink, R. G.,Van Der Plas, S. E.,Visser, M., Weijs, P. J. Effect of a high protein diet and/or resistance exercise on preservation of fat free mass during weight loss in overweight older adults: a randomized controlled trial. Clinical nutrition (edinburgh, scotland). 2015. 34:S206- https://www.cochranelibrary.com/central/doi/10.1002/central/CN-01128963/full | X | X | | | X
570. | Vieillevoye, S.,Poortmans, J. R.,Duchateau, J.,Carpentier, A. Effects of a combined essential amino acids/carbohydrate supplementation on muscle mass, architecture and maximal strength following heavy-load training. Eur J Appl Physiol. 2010. 110:479–88 https://www.ncbi.nlm.nih.gov/pubmed/20521064 20521064 | | X | | | | | | X
571. | Vila, R.,Granada, M. L.,Gutierrez, R. M.,Fernandez-Lopez, J. A.,Remesar, X., Formiguera, X.,Foz, M.,Alemany, M. Short-term effects of a hypocaloric diet on nitrogen excretion in morbid obese women. Eur J Clin Nutr. 2001. 55:186–91 https://www.ncbi.nlm.nih.gov/pubmed/11305267 11305267 | | X | | X
572. | Villareal, D. T.,Chode, S.,Parimi, N.,Sinacore, D. R.,Hilton, T.,Armamento-Villareal, R.,Napoli, N.,Qualls, C.,Shah, K. Weight loss, exercise, or both and physical function in obese older adults. N Engl J Med. 2011. 364:1218–29 https://www.ncbi.nlm.nih.gov/pubmed/21449785 21449785 | | X
573. | Villeneuve, N.,Pelletier-Beaumont, E.,Nazare, J. A.,Lemieux, I.,Almeras, N., Bergeron, J.,Tremblay, A.,Poirier, P.,Despres, J. P. Interrelationships between changes in anthropometric variables and computed tomography indices of abdominal fat distribution in response to a 1-year physical activity-healthy eating lifestyle modification program in abdominally obese men. Appl Physiol Nutr Metab. 2014. 39:503–11 https://www.ncbi.nlm.nih.gov/pubmed/24669993 24669993 | | X
574. | Vogt, M.,Puntschart, A.,Howald, H.,Mueller, B.,Mannhart, C.,Gfeller-Tuescher, L., Mullis, P.,Hoppeler, H. Effects of dietary fat on muscle substrates, metabolism, and performance in athletes. Med Sci Sports Exerc. 2003. 35:952–60 https://www.ncbi.nlm.nih.gov/pubmed/12783043 12783043 | | | | | | | | X
575. | Volpi, E.,Kobayashi, H.,Sheffield-Moore, M.,Mittendorfer, B.,Wolfe, R. R. Essential amino acids are primarily responsible for the amino acid stimulation of muscle protein anabolism in healthy elderly adults. Am J Clin Nutr. 2003. 78:250–8 https://www.ncbi.nlm.nih.gov/pubmed/12885705 12885705 | | X
576. | Vorup, J.,Pedersen, M. T.,Brahe, L. K.,Melcher, P. S.,Alstrøm, J. M.,Bangsbo, J. Effect of small-sided team sport training and protein intake on muscle mass, physical function and markers of health in older untrained adults: A randomized trial. PLoS ONE. 2017. 12:#pages# http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L618693439 10.1371/journal.pone.0186202 | | X
577. | Wakabayashi, H.,Takahashi, R.,Murakami, T. The Prevalence and Prognosis of Sarcopenic Dysphagia in Patients Who Require Dysphagia Rehabilitation. J Nutr Health Aging. 2019. 23:84–88 https://www.ncbi.nlm.nih.gov/pubmed/30569074 30569074 | | X
578. | Waldman, H. S.,Smith, J. W.,Lamberth, J.,Fountain, B. J.,McAllister, M. J. A 28-Day Carbohydrate-Restricted Diet Improves Markers of Cardiometabolic Health and Performance in Professional Firefighters. J Strength Cond Res. 2019. #volume#:#pages# https://www.ncbi.nlm.nih.gov/pubmed/31469768 | | | | X
579. | Walker, J. L.,Heigenhauser, G. J. F.,Hultman, E.,Spriet, L. L. Dietary carbohydrate, muscle glycogen content, and endurance performance in well-trained women. Journal of Applied Physiology. 2000. 88:2151–2158 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L30453922 10846030 | | | | | | | | X
580. | Walrand, S.,Short, K. R.,Bigelow, M. L.,Sweatt, A. J.,Hutson, S. M.,Nair, K. S. Functional impact of high protein intake on healthy elderly people. American Journal of Physiology - Endocrinology and Metabolism. 2008. 295:E921–E928 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L352757848 10.1152/ajpendo.90536.2008 18697911 | | X | | X
581. | Wang, C. C.,Adochio, R. L.,Leitner, J. W.,Abeyta, I. M.,Draznin, B.,Cornier, M. A. Acute effects of different diet compositions on skeletal muscle insulin signalling in obese individuals during caloric restriction. Metabolism. 2013. 62:595–603 https://www.ncbi.nlm.nih.gov/pubmed/23174405 23174405 | | | | X
582. | Wang, H. L.,Ding, T. T.,Lu, S.,Xu, Y.,Tian, J.,Hu, W. F.,Zhang, J. Y. Muscle mass loss and intermuscular lipid accumulation were associated with insulin resistance in patients receiving hemodialysis. Chinese Medical Journal. 2013. 126:4612–4617 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L370492114 10.3760/cma.j.issn.0366-6999.20130976 24342298 | | X | | | | | | X
583. | Waters, D. L.,Vawter, R.,Qualls, C.,Chode, S.,Armamento-Villareal, R.,Villareal, D. T. Long-term maintenance of weight loss after lifestyle intervention in frail, obese older adults. J Nutr Health Aging. 2013. 17:3–7 https://www.ncbi.nlm.nih.gov/pubmed/23299370 23299370 | | X
584. | Weinheimer, E. M.,Conley, T. B.,Kobza, V. M.,Sands, L. P.,Lim, E.,Janle, E. M., Campbell, W. W. Whey protein supplementation does not affect exercise training-induced changes in body composition and indices of metabolic syndrome in middle-aged overweight and obese adults. Journal of Nutrition. 2012. 142:1532–1539 http://www.embase.com/search/results?subaction=viewrecord&from=export&id=L365646739 10.3945/jn.111.153619 | | X
585. | Welch, A. A. Nutritional influences on age-related skeletal muscle loss. Proc Nutr Soc. 2014. 73:16–33 https://www.ncbi.nlm.nih.gov/pubmed/24229650 24229650 | X
586. | Welch, A. A.,MacGregor, A. J.,Minihane, A. M.,Skinner, J.,Valdes, A. A.,Spector, T. D.,Cassidy, A. Dietary fat and fatty acid profile are associated with indices of skeletal muscle mass in women aged 18-79 years. J Nutr. 2014. 144:327–34 https://www.ncbi.nlm.nih.gov/pubmed/24401817 24401817 | X
587. | Welch, A. A.,MacGregor, A. J.,Skinner, J.,Spector, T. D.,Moayyeri, A.,Cassidy, A. A higher alkaline dietary load is associated with greater indexes of skeletal muscle mass in women. Osteoporos Int. 2013. 24:1899–908 https://www.ncbi.nlm.nih.gov/pubmed/23152092 23152092 | X | X
588. | Wesseltoft-Rao, N.,Hjermstad, M. J.,Ikdahl, T.,Dajani, O.,Ulven, S. M.,Iversen, P. O.,Bye, A. Comparing two classifications of cancer cachexia and their association with survival in patients with unresected pancreatic cancer. Nutr Cancer. 2015. 67:472–80 https://www.ncbi.nlm.nih.gov/pubmed/25710201 25710201 | | X | | | | | | X
589. | White, K. M.,Bauer, S. J.,Hartz, K. K.,Baldridge, M. Changes in body composition with yogurt consumption during resistance training in women. Int J Sport Nutr Exerc Metab. 2009. 19:18–33 https://www.ncbi.nlm.nih.gov/pubmed/19403951 19403951 | | X
590. | Wilcox, G.,Strauss, B. J.,Francis, D. E.,Upton, H.,Boneh, A. Body composition in young adults with inborn errors of protein metabolism--a pilot study. J Inherit Metab Dis. 2005. 28:613–26 https://www.ncbi.nlm.nih.gov/pubmed/16151892 16151892 | | X | | | | | | X
591. | Witbracht, M. G.,Laugero, K. D.,Van Loan, M. D.,Adams, S. H.,Keim, N. L. Performance on the Iowa Gambling Task is related to magnitude of weight loss and salivary cortisol in a diet-induced weight loss intervention in overweight women. Physiol Behav. 2012. 106:291–7 https://www.ncbi.nlm.nih.gov/pubmed/21565212 21565212 | | X | | X
592. | Woo, J.,Chan, R.,Ong, S.,Bragt, M.,Bos, R.,Parikh, P.,de Groot, L. C. Randomized Controlled Trial of Exercise and Nutrition Supplementation on Physical and Cognitive Function in Older Chinese Adults Aged 50 Years and Older. J Am Med Dir Assoc. 2019. #volume#:#pages# https://www.ncbi.nlm.nih.gov/pubmed/31558379 | | X
593. | Woo, J.,Leung, J.,Sham, A.,Kwok, T. Defining sarcopenia in terms of risk of physical limitations: a 5-year follow-up study of 3,153 chinese men and women. J Am Geriatr Soc. 2009. 57:2224–31 https://www.ncbi.nlm.nih.gov/pubmed/19925615 19925615 | | X
594. | Wood, R. J.,Gregory, S. M.,Sawyer, J.,Milch, C. M.,Matthews, T. D.,Headley, S. A. Preservation of fat-free mass after two distinct weight loss diets with and without progressive resistance exercise. Metab Syndr Relat Disord. 2012. 10:167–74 https://www.ncbi.nlm.nih.gov/pubmed/22283635 22283635 | | | | X
595. | Woods, J. L.,Iuliano-Burns, S.,Walker, K. Z. Weight loss in elderly women in low-level care and its association with transfer to high-level care and mortality. Clin Interv Aging. 2011. 6:311–7 https://www.ncbi.nlm.nih.gov/pubmed/22267919 22267919 | | X
596. | Woods, J. L.,Iuliano-Burns, S.,Walker, K. Z. Immunological and nutritional factors in elderly people in low-level care and their association with mortality. Immun Ageing. 2013. 10:32 https://www.ncbi.nlm.nih.gov/pubmed/23915335 23915335 | | X | | X
597. | Wouters-Wesseling, W.,Van Hooijdonk, C.,Wagenaar, L.,Bindels, J.,de Groot, L., Van Staveren, W. The effect of a liquid nutrition supplement on body composition and physical functioning in elderly people. Clin Nutr. 2003. 22:371–7 https://www.ncbi.nlm.nih.gov/pubmed/12880604 12880604 | | X
598. | Wright, C. S.,Zhou, J.,Sayer, R. D.,Kim, J. E.,Campbell, W. W. Effects of a High-Protein Diet Including Whole Eggs on Muscle Composition and Indices of Cardiometabolic Health and Systemic Inflammation in Older Adults with Overweight or Obesity: A Randomized Controlled Trial. Nutrients. 2018. 10:#pages# https://www.ncbi.nlm.nih.gov/pubmed/30041437 | | | | X
599. | Wycherley, T. P.,Buckley, J. D.,Noakes, M.,Clifton, P. M.,Brinkworth, G. D. Comparison of the effects of weight loss from a high-protein versus standard-protein energy-restricted diet on strength and aerobic capacity in overweight and obese men. Eur J Nutr. 2013. 52:317–25 https://www.ncbi.nlm.nih.gov/pubmed/22406907 22406907 | | | | X
600. | Wycherley, T. P.,Buckley, J. D.,Noakes, M.,Clifton, P. M.,Brinkworth, G. D. Long-term effects of a very low-carbohydrate weight loss diet on exercise capacity and tolerance in overweight and obese adults. J Am Coll Nutr. 2014. 33:267–73 https://www.ncbi.nlm.nih.gov/pubmed/24988413 24988413 | | | | X
601. | Xenaki, N.,Bacopoulou, F.,Kokkinos, A.,Nicolaides, N. C.,Chrousos, G. P.,Darviri, C. Impact of a stress management program on weight loss, mental health and lifestyle in adults with obesity: a randomized controlled trial. J Mol Biochem. 2018. 7:78–84 https://www.ncbi.nlm.nih.gov/pubmed/30568922 30568922 | | X | | X
602. | Xu, B.,Houston, D. K.,Locher, J. L.,Ellison, K. J.,Gropper, S.,Buys, D. R.,Zizza, C. A. Higher Healthy Eating Index-2005 scores are associated with better physical performance. J Gerontol A Biol Sci Med Sci. 2012. 67:93–9 https://www.ncbi.nlm.nih.gov/pubmed/22042723 22042723 | X
603. | Xu, F.,Letendre, J.,Bekke, J.,Beebe, N.,Mahler, L.,Lofgren, I. E.,Delmonico, M. J. Impact of a program of Tai Chi plus behaviorally based dietary weight loss on physical functioning and coronary heart disease risk factors: a community-based study in obese older women. J Nutr Gerontol Geriatr. 2015. 34:50–65 https://www.ncbi.nlm.nih.gov/pubmed/25803604 25803604 | X | X
604. | Yagi, S.,Kadota, M.,Aihara, K. I.,Nishikawa, K.,Hara, T.,Ise, T.,Ueda, Y.,Iwase, T., Akaike, M.,Shimabukuro, M.,Katoh, S.,Sata, M. Association of lower limb muscle mass and energy expenditure with visceral fat mass in healthy men. Diabetol Metab Syndr. 2014. 6:27 https://www.ncbi.nlm.nih.gov/pubmed/24571923 24571923 | X | X
605. | Yamauti, A. K.,Ochiai, M. E.,Bifulco, P. S.,de Araujo, M. A.,Alonso, R. R.,Ribeiro, R. H.,Pereira-Barretto, A. C. Subjective global assessment of nutritional status in cardiac patients. Arq Bras Cardiol. 2006. 87:772–7 https://www.ncbi.nlm.nih.gov/pubmed/17262116 17262116 | X | X | | | | | | X
606. | Yang, L. J.,Wu, G. H.,Yang, Y. L.,Wu, Y. H.,Zhang, L.,Wang, M. H.,Mo, L. Y.,Xue, G.,Wang, C. Z.,Weng, X. F. Nutrition, Physical Exercise, and the Prevalence of Sarcopenia in Elderly Residents in Nursing Homes in China. Med Sci Monit. 2019. 25:4390–4399 https://www.ncbi.nlm.nih.gov/pubmed/31189870 31189870 | X
607. | Yates, S. M.,Dunnagan, T. A. Evaluating the effectiveness of a home-based fall risk reduction program for rural community-dwelling older adults. J Gerontol A Biol Sci Med Sci. 2001. 56:M226–30 https://www.ncbi.nlm.nih.gov/pubmed/11283195 11283195 | | X
608. | Yeo, W. K.,Lessard, S. J.,Chen, Z. P.,Garnham, A. P.,Burke, L. M.,Rivas, D. A., Kemp, B. E.,Hawley, J. A. Fat adaptation followed by carbohydrate restoration increases AMPK activity in skeletal muscle from trained humans. J Appl Physiol (1985). 2008. 105:1519–26 https://www.ncbi.nlm.nih.gov/pubmed/18801964 18801964 | | | | X | | | | X
609. | Yokoyama, Y.,Nishi, M.,Murayama, H.,Amano, H.,Taniguchi, Y.,Nofuji, Y.,Narita, M.,Matsuo, E.,Seino, S.,Kawano, Y.,Shinkai, S. Dietary Variety and Decline in Lean Mass and Physical Performance in Community-Dwelling Older Japanese: A 4-year Follow-Up Study. J Nutr Health Aging. 2017. 21:11–16 https://www.ncbi.nlm.nih.gov/pubmed/27999844 27999844 | | | | X
610. | Yong, M. H.,Shin, J. I.,Yang, D. J.,Yang, Y. A. Comparison of Physical Fitness Status between Middle-aged and Elderly Male Laborers According to Lifestyle Behaviors. J Phys Ther Sci. 2014. 26:1965–9 https://www.ncbi.nlm.nih.gov/pubmed/25540509 25540509 | X | X
611. | Yoo, J. I.,Ha, Y. C.,Kwon, H. B.,Lee, Y. K.,Koo, K. H.,Yoo, M. J. High Prevalence of Sarcopenia in Korean Patients after Hip Fracture: a Case-Control Study. J Korean Med Sci. 2016. 31:1479–84 https://www.ncbi.nlm.nih.gov/pubmed/27510394 27510394 | | X
612. | Yoshii, N.,Sato, K.,Ogasawara, R.,Kurihara, T.,Hamaoka, T.,Fujita, S. Relationship between Dietary Protein or Essential Amino Acid Intake and Training-Induced Muscle Hypertrophy among Older Individuals. J Nutr Sci Vitaminol (Tokyo). 2017. 63:379–388 https://www.ncbi.nlm.nih.gov/pubmed/29332899 29332899 | | X | | X
613. | Yoshimura, E.,Kumahara, H.,Tobina, T.,Matsuda, T.,Watabe, K.,Matono, S.,Ayabe, M.,Kiyonaga, A.,Anzai, K.,Higaki, Y.,., Aerobic exercise attenuates the loss of skeletal muscle during energy restriction in adults with visceral adiposity. Obesity facts. 2014. 7:26–35 https://www.cochranelibrary.com/central/doi/10.1002/central/CN-00986322/full 24457527 | | X
614. | Z. Movassagh E,Kontulainen, S.,Baxter-Jones, A. D. G.,Whiting, S.,Szafron, M., Papadimitropoulos, M.,Vatanparast, H. Are milk and alternatives and fruit and vegetable intakes during adolescence associated with cortical and trabecular bone structure, density, and strength in adulthood?. Osteoporos Int. 2017. 28:609–619 https://www.ncbi.nlm.nih.gov/pubmed/27699440 27699440 | | X | | X
615. | Zajac, A.,Poprzecki, S.,Maszczyk, A.,Czuba, M.,Michalczyk, M.,Zydek, G. The effects of a ketogenic diet on exercise metabolism and physical performance in off-road cyclists. Nutrients. 2014. 6:2493–508 https://www.ncbi.nlm.nih.gov/pubmed/24979615 24979615 | | | | X
616. | Zbeida, M.,Goldsmith, R.,Shimony, T.,Vardi, H.,Naggan, L.,Shahar, D. R. Mediterranean diet and functional indicators among older adults in non-Mediterranean and Mediterranean countries. J Nutr Health Aging. 2014. 18:411–8 https://www.ncbi.nlm.nih.gov/pubmed/24676323 24676323 | X
617. | Zhu, J.,Xiang, Y. B.,Cai, H.,Li, H.,Gao, Y. T.,Zheng, W.,Shu, X. O. A Prospective Investigation of Dietary Intake and Functional Impairments Among the Elderly. Am J Epidemiol. 2018. 187:2372–2386 https://www.ncbi.nlm.nih.gov/pubmed/30060001 30060001 | | | | X
618. | Zhu, K.,Kerr, D. A.,Meng, X.,Devine, A.,Solah, V.,Binns, C. W.,Prince, R. L. Two-Year Whey Protein Supplementation Did Not Enhance Muscle Mass and Physical Function in Well-Nourished Healthy Older Postmenopausal Women. J Nutr. 2015. 145:2520–6 https://www.ncbi.nlm.nih.gov/pubmed/26400966 26400966 | | X
619. | Zhu, N.,Jacobs, D. R.,Meyer, K. A.,He, K.,Launer, L.,Reis, J. P.,Yaffe, K.,Sidney, S.,Whitmer, R. A.,Steffen, L. M. Cognitive function in a middle aged cohort is related to higher quality dietary pattern 5 and 25 years earlier: the CARDIA study. J Nutr Health Aging. 2015. 19:33–8 https://www.ncbi.nlm.nih.gov/pubmed/25560814 25560814 | | X | | X
620. | Zonta, M. L.,Oyhenart, E. E.,Navone, G. T. Nutritional vulnerability in Mbya-Guarani adolescents and adults from Misiones, Argentina. Am J Hum Biol. 2011. 23:592–600 https://www.ncbi.nlm.nih.gov/pubmed/21681847 21681847 | X

xi Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

xii Institute of Medicine. Dietary Reference Intakes for Energy, Carbohydrate, Fiber, Fat, Fatty Acids, Cholesterol, Protein, and Amino Acids. Washington (DC): The National Academies Press; 2002.

xiii Macronutrient percent of energy outside of the AMDR are as follows:

- Carbohydrate for all age groups: <45 or >65 percent of energy;
- Protein for children, 1-3y: <5 or >20 percent of energy, Protein for children, 4-18y: <10 or >30 percent of energy, Protein for adults, age 19y and older: <10 or >35 percent of energy;
- Fat for children, 1-3y: <30 or >40 percent of energy, Fat for children, 4-18y: <25 or >35 percent of energy, Fat for adults, age 19y and older: <20 or >35 percent of energy.

xiv The Human Development classification was based on the Human Development Index (HDI) ranking from the year the study intervention occurred or data were collected (UN Development Program. HDI 1990-2017 HDRO calculations based on data from UNDESA (2017a), UNESCO Institute for Statistics (2018), United Nations Statistics Division (2018b), World Bank (2018b), Barro and Lee (2016) and IMF (2018). Available from: http://hdr.undp.org/en/data). If the study did not report the year in which the intervention occurred or data were collected, the HDI classification for the year of publication was applied. HDI values are available from 1980, and then from 1990 to present. If a study was conducted prior to 1990, the HDI classification from 1990 was applied. If a study was conducted in 2018 or 2019, the most current HDI classification was applied. When a country was not included in the HDI ranking, the current country classification from the World Bank was used instead (The World Bank. World Bank country and lending groups. Available from: https://datahelpdesk.worldbank.org/knowledgebase/articles/906519-world-country-and-lending-groups).