# WHAT IS THE RELATIONSHIP BETWEEN DIETARY PATTERNS CONSUMED AND SARCOPENIA?

## PLAIN LANGUAGE SUMMARY

### What is the question?

- The question is: What is the relationship between dietary patterns consumed and sarcopenia?

### What is the answer to the question?

Dietary patterns

- Insufficient evidence is available to determine the relationship between dietary patterns and sarcopenia in older adults.

Diets based on macronutrient distribution

- Insufficient evidence was available to determine the relationship between diets based on macronutrient distribution and sarcopenia.

### Why was this question asked?

- This important public health question was identified by the U.S. Departments of Agriculture (USDA) and Health and Human Services (HHS) to be examined by the 2020 Dietary Guidelines Advisory Committee.

### How was this question answered?

- The 2020 Dietary Guidelines Advisory Committee, Dietary Patterns Subcommittee conducted a systematic review to answer this question with support from the Nutrition Evidence Systematic Review (NESR) team.
- Dietary patterns were defined as the quantities, proportions, variety, or combination of different foods, drinks, and nutrients (when available) in diets, and the frequency with which they are habitually consumed.
- Diets based on macronutrient distribution were examined when at least one macronutrient proportion was outside of the acceptable macronutrient distribution range (AMDR) for carbohydrate, fat, and/or protein.

### What is the population of interest?

- For the intervention/exposure, adolescents through older adults
- For the outcome, adults and older adults

### What evidence was found?

- This review identified 4 articles that met inclusion criteria.
- Four articles examined dietary patterns and sarcopenia.
- Two articles also examined diets based on macronutrient distribution and sarcopenia.
- Studies differed in dietary pattern methods, macronutrient distributions, and assessment of sarcopenia.
- Results from the included studies were inconsistent.
- Several limitations in the study design and conduct of included articles were identified. This includes a lack of accounting for potential confounders or possible changes in dietary intake over time.
- The 2020 Committee could not draw conclusions due to limitations in and lack of evidence.

### How up-to-date is this systematic review?

- This review searched for studies from January, 2000 and October, 2019.

## FULL REVIEW

### Systematic review question

What is the relationship between dietary patterns consumed and sarcopenia?

### Conclusion statements and grades

#### Dietary patterns

Insufficient evidence is available to determine the relationship between dietary patterns and sarcopenia in older adults. (Grade: Grade not assignable)

#### Diets based on macronutrient distribution

Insufficient evidence was available to determine the relationship between diets based on macronutrient distribution and sarcopenia. (Grade: Grade not assignable)

### Summary of the evidence

- This systematic review includes 4 prospective cohort studies that examined the relationship between dietary patterns and sarcopenia, 2 of which also examined diets based on macronutrient distribution, that met inclusion criteria and were published between January 2000 and October 2019.^1–4^
  ○ Two of the studies reported macronutrient distributions in which the percent of energy from fat was higher than the AMDR.^2,3^
  ○ Dietary patterns were defined as the quantities, proportions, variety, or combination of different foods, drinks, and nutrients (when available) in diets, and the frequency with which they are habitually consumed.
  ○ Diets based on macronutrient distribution were examined when at least one macronutrient proportion was outside of the acceptable macronutrient distribution range (AMDR) for carbohydrate, fat, and/or protein. When describing and categorizing studies included in this review, the Committee did not label the diets examined as “low” or “high,” because no universally accepted, standard definition is currently available, for example, for “low-carbohydrate” or “high-fat” diets. Instead, the Committee focused on whether, and the extent to which, the proportions of the macronutrients were below or above the AMDR.
- The studies were inconsistent, both in terms of which dietary patterns or macronutrient distributions that were examined, how dietary intake was assessed, assessment of sarcopenia, and results reported regarding the association between dietary patterns and risk of sarcopenia. In addition, the studies had relatively small sample sizes with few cases of sarcopenia.
- The body of evidence had several risks of bias, including lack of adjustment for all potential confounders, and assessment of diet only once at baseline, and lack of accounting for possible changes in dietary intake that may have occurred over follow-up.
- The studies were direct and generalizable, in that that the intervention, comparators, and outcomes of interest in the included studies are directly related to the systematic review question, and are applicable to the U.S. population. However, study participants may have been healthier than the average older adult.

### Description of the evidence

This systematic review includes 4 prospective cohort studies that examine the relationship between dietary patterns and sarcopenia, 2 of which also examined diets based on macronutrient distribution that met inclusion criteria, and were published between January 2000 and October 2019 (Table 1).^1–4^

#### Population/participant characteristics

The studies included in this systematic review were conducted in China,^1^ Finland,^3^ Sweden,^4^ and the United Kingdom.^2^ Sample size ranged from 254 to 2948 participants. Two studies included both men and women,^1,2^ one study included only women,^3^ and one study included only men.^4^ Mean age of participants at baseline ranged from approximately 68 years to >85 years.

#### Intervention/exposure

Included studies examined dietary patterns using a variety of methods. One study identified dietary patterns using factor analysis,^1^ one study identified dietary patterns using cluster analysis,^2^ and 3 studies examined adherence to dietary patterns using 6 different indices or scores.^1,3,4^ Two studies^2,3^ examined dietary patterns in which the proportion of energy from fat was above the AMDR in at least one of the exposure groups compared (i.e., each cluster^2^ or third quartile^3^).

Dietary intake was assessed using a variety of validated methods, including a foodfrequency questionnaire,^1^ 24-hour dietary recall using a multiple pass method,^2^ and 3-day^3^ or 7-day^4^ food records. In all studies, diet was assessed once, at baseline.

#### Outcome assessment

All included studies examined risk of developing sarcopenia, with follow-up ranging from 3-4 years^1–3^ to 16 years.^4^

One study defined sarcopenia using the Asian Working Group for Sarcopenia algorithm,^1^ and 3 studies defined sarcopenia using the European Working Group on Sarcopenia in Older People (EWGSOP) criteria.^2–4^ In all of the included studies, sarcopenia was defined as low muscle mass with low muscle strength (based on handgrip strength) and/or low muscle performance (based on walking speed). However, Isanejad et al^3^ included participants considered to be pre-sarcopenic (low muscle mass only) or sarcopenic in analyses.^3^

### Evidence synthesis

Results reported in the studies included in this systematic review were mixed (Table 2). Chan et al^1^ analyzed data from a prospective cohort study from Hong Kong that included both men and women (51% female), aged ~72 years.^1^ Five dietary patterns were examined, including 2 dietary patterns based on an index/score (Dietary Quality Index-International score (DQI-I), Mediterranean Diet Score (MDS)), and 3 identified via factor analysis (“Vegetables-Fruits”, “Snacks-Drinks-Milk Products”, and “Meat-Fish”). None of the dietary patterns examined were significantly associated with risk of sarcopenia after 4 years of follow-up.^1^

Granic et al^2^ analyzed data from a prospective cohort study from the United Kingdom that included both men and women (62% female), all over 85 years of age.^2^ Three dietary patterns were examined, that were identified via cluster analyses (‘Low Red Meat’, ‘Traditional British’, ‘Low Butter’). All 3 patterns had a mean percent energy from fat higher than the AMDR. Adherence to a ‘Traditional British’ compared to a ‘Low Butter’ dietary pattern at >85 years was associated with higher risk of prevalent sarcopenia at 3 year follow-up. However, it was not significantly associated with incident sarcopenia. Adherence to a ‘Low Red Meat’ compared to a ‘Low Butter’ dietary pattern was not significantly associated with risk of prevalent or incident sarcopenia. In addition, results were similar when stratified by protein intake >1 or <1g/kg adjusted body weight/day.^2^

Isanejad et al^3^ analyzed data from a prospective cohort study from Finland that included only women, aged ~68 years.^3^ Two dietary patterns were examined that were based on an index/score (Baltic Sea Diet Score (BSD) and MDS. For the BSD score, one quartile had percent energy from fat higher than the AMDR. Higher BSD score (categorical) at 68 years was significantly associated with reduced risk of sarcopenia after 3 year follow-up. However, associations were not significant when BSD was analyzed continuously. MDS score at 68 years was not significantly associated with risk of sarcopenia after 3 year follow-up when analyzed either continuously or categorically. In this study, pre-sarcopenic and sarcopenic women were combined, and analyzed together.^3^

Karlsson et al^4^ analyzed data from a prospective cohort study from Sweden that included only men, aged ~71 years.^4^ Two dietary patterns were examined that were based on an index/score (Modified Healthy Diet Indicator (mHDI), modified Mediterranean Diet Score (mMDS)). Higher mHDI score (medium vs. low) at 71 years was significantly associated with lower risk of sarcopenia at 87 years. However, high vs. low score and analysis of scores continuously were not significantly associated with risk of sarcopenia. Higher mMDS score (continuous) at 71 years was associated with lower risk of sarcopenia at 87 years. However, when mMDS scores were analyzed categorically (low vs. medium or high), there were no significant associations with risk of sarcopenia.^4^

#### Assessment of the evidence^ii^

This systematic review included only 4 studies that met inclusion criteria, and all were prospective cohort studies. It was determined that this body of evidence was insufficient to draw conclusions about the relationship between dietary patterns and risk of sarcopenia, or diets based on macronutrient distribution and risk of sarcopenia. As outlined and described in detail below, the body of evidence was assessed for the following elements used when grading the strength of evidence.

- Risk of bias: The included articles had a number of potential risks of bias, or limitations, that make interpretation of results difficult (Table 1; Table 3). While studies adjusted for a number of potential confounders, they did not adjust for all key confounders, such as race/ethnicity or physical disability. These studies examined dietary patterns only once at baseline, and did not account for possible changes in dietary intake that may have occurred over follow-up. In addition, the studies enrolled older individuals, and did not account for dietary patterns consumed earlier in life. None of the studies accounted for missing data, either due to lost to follow-up or criteria used when selecting subjects into the analyses. Attrition due to mortality was not reported by the included articles. The studies are also prone to selection bias. Though subjects enrolled in the study were intended to be representative of the general population in the country or region where the study was conducted, they likely represent healthier individuals (i.e., those able to walk, take public transportation, or with interest in preventing future falls or fracture). Finally, none of the studies had preregistered statistical plans, and therefore, there is potential for selective outcome reporting.
- Consistency: The studies were inconsistent, both in terms of which dietary patterns were examined, how dietary intake was assessed, assessment of sarcopenia, and results reported regarding the association between dietary patterns and risk of sarcopenia.
- Directness: The populations, intervention, comparators, and outcomes of interest in the included studies are directly related to the systematic review question.
- Precision: The studies had small analytic sample sizes with relatively few sarcopenia cases. The width of confidence intervals indicates imprecision within the body of evidence.
- Generalizability: The interventions and/or exposures, comparators, and outcomes examined in the body of evidence are applicable to the U.S. population. However, study participants may have been healthier than the average older adult (i.e., those able to walk, take public transportation, or with interest in preventing future falls or fracture)

### Research recommendations

In order to better assess the relationship between dietary patterns and sarcopenia, future research may:

1. Assess information regarding diet at more than one time-point, preferably during the course of follow-up, to facilitated determining the relationship between dietary. patterns over time and sarcopenia.
2. Examine the relationship between dietary patterns earlier in life and risk of sarcopenia.
3. Provide sufficient information, definitions or standards, and repeated measures on the quantification, i.e., types and amounts of foods/food groups such as fruits and vegetables, and beverages such as alcohol, consumed when examining the relationship between dietary patterns and/or diets based on macronutrient distribution and sarcopenia.
4. Include diverse populations with varying race/ethnicity, age, sex/gender, socioeconomic background, and chronic disease status, while ensuring to report the racial/ethnic background of participants studied.

### Included articles

1 Chan R, Leung J, Woo J. A prospective cohort study to examine the association between dietary patterns and sarcopenia in Chinese community-dwelling older people in Hong Kong. J Am Med Dir Assoc. 2016;17(4):336–342. doi:10.1016/j.jamda.2015.12.004.26774365
2 Granic A, Mendonca N, Sayer AA, . Effects of dietary patterns and low protein intake on sarcopenia risk in the very old: the Newcastle 85+ study. Clin Nutr. 2020;39(1):166–173. doi:10.1016/j.clnu.2019.01.009.30709690
3 Isanejad M, Sirola J, Mursu J, . Association of the Baltic Sea and Mediterranean diets with indices of sarcopenia in elderly women, OSPTRE-FPS study. Eur J Nutr. 2018;57(4):1435–1448. doi:10.1007/s00394-017-1422-2.28303397
4 Karlsson M, Becker W, Michaelsson K, Cederholm T, Sjogren P. Associations between dietary patterns at age 71 and the prevalence of sarcopenia 16 years later. Clin Nutr. 2020;39(4):1077–1084. doi:10.1016/j.clnu.2019.04.009.31036414

Table 1 Description of studies that examined the relationship between dietary patterns and diets based on macronutrient distribution and sarcopenia^iii^

Study and Participant Characteristics | Intervention/Exposure and Outcomes | Results | Confounding, Study Limitations, and Summary of Findings
Chan, 2016 ^1^; PCS (Mr. Os and Ms Os), Hong Kong, China; Analytic N: 2948 (Attrition: 26%); Sex: 51% female; Age: 72.4 y [5.0]; Anthropometry: mean BMI 23.6 kg/m^2^ [3.1]; Physical activity: Physical activity scale for the elderly (PASE): 91.2 [39.8]; SES: Education: 71.5% primary or below; Marital status: ~70% married or cohabited; Alcohol: ~12% currently drink alcohol | Dietary patterns:; Adherence to 5 dietary patterns was examined:; - 2 dietary patterns were examined using an index/score:; ○ Dietary Quality Index-International score (DQI-I)^iv^; ■ Positive components: Vegetables, fruit, grain, fiber, protein, iron, calcium, vitamin C, overall food group variety, within food group variety; ■ Moderation components: Total fat, SFA, cholesterol, sodiu, empty calorie foods, macronutrient ratio, fatty acid ratio; ○ Mediterranean Diet Score (MDS)^v^; ■ Positive components: Vegetables, legumes, fruit and nuts, cereals, fish, MUFA:SFA ratio; ■ Negative components: Red and processed meat, dairy products; ■ Moderation components: Alcohol; - 3 dietary patterns identified via factor analysis:; ○ “Vegetables-Fruits”: Higher in tomatoes, dark green and leafy vegetables, cruciferous vegetables, starchy vegetables, other vegetables, soy, fruits, legumes, mushroom and fungi, and lower in fats and oils; ○ “Snacks-Drinks-Milk Products”: Higher in condiments, coffee, fast food, nuts, French fries and potato chips, milk and milk products, whole grains, sweets and desserts, beverage; ○ “Meat-Fish”: Higher in dim sum, red and processed meats, poultry, fish and seafood, wine , and lower in refined grains; Dietary assessment methods: Validated FFQ at baseline, age ~72y; Outcome assessment methods: Sarcopenia was defined according to the Asian Working Group for Sarcopenia algorithm:; - Low muscle mass: Appendicular skeletal muscle mass (ASM) index, ASM/height^2^ <7.0 kg/m^2^ for men, <5.4 kg/m^2^ for women; - Low muscle strength: Grip strength <26 kg for men, <18g for women; - Low physical performance: Gait speed <0.8 m/s for men and women | [underlined: Significant]: N/A; [underlined: Non-Significant]:; In men (n=1449), dietary patterns at 72y and sarcopenia at 4y f/u:; - DQI-I: OR: 1.00, 95% CI: 0.98, 1.02, p=0.670, NS; - MDS: OR: 0.98, 95% CI: 0.86, 1.10, P=0.678, NS; - Vegetables-fruits: OR: 1.07, 95% CI: 0.88, 1.29, p=0.522, NS; - Snacks-drinks-milk products: OR: 0.95, CI: 0.78, 1.16, p=0.611, NS; - Meat-fish: OR: 1.00, 95% CI: 0.84, 1.20, p=1.000, NS; In women (n=1499), dietary patterns at 72y and sarcopenia at 4y f/u:; - DQI-I: OR: 0.99, CI: 0.97, 1.02, p=0.611, NS; - MDS: OR: 0.96, CI: 0.83, 1.11, p=0.602, NS; - Vegetables-fruits: OR: 1.15, CI: 0.94, 1.40, p=0.190, NS; - Snacks-drinks-milk products: OR: 1.20, CI: 0.94, 1.53, p=0.148, NS; Meat-fish: OR: 1.10, CI: 0.87, 1.40, p=0.415, NS | Key confounders accounted for:; Sex; Age; SES; Race/ethnicity; Anthropometry; Physical activity; Other: Depression; Neurodegenerative disorders; Osteoporosis; Smoking; Alcohol; Number of chronic diseases; Limitations:; - Did not account for the following key confounders: Race/ethnicity; Physical disability; - Only included subjects able to walk and take public transportation; exposure occurred prior to start of f/u; - Only assessed dietary intake once at baseline; did not account for possible changes in dietary intake over f/u; - Did not account for missing data; - No published protocol; potential for selective outcome reporting; Funding Sources:; Council of Hong Kong, Hong Kong Jockey Club Charities Trust, The Chinese University of Hong Kong; Summary: Adherence to the DQI-I, MDS, ‘vegetables-fruits’, ‘snacks-drinks-milk products’, or ‘meat-fish’ dietary patterns at 72y was not significantly associated with risk of sarcopenia after 4y f/u.
Granic, 2019 ^2^; PCS (The Newcastle 85+ Study), United Kingdom; Analytic N: 373 (Attrition: 64%); Age: ≥85y; Sex: 62% female; SES: 51% manual occupation; 64% 0-9y education; 69% married; Anthropometry: 40% overweight/obese; Dietary protein intake: 63.75 g/d; Physical activity: 19% low, 45% moderate, 36% high | Dietary patterns:; Adherence to 3 dietary patterns identified via cluster analysis:; - ‘Low Red Meat’: lower in legumes, sweets and desserts, and higher in fish/seafood; - ‘Traditional British’: higher in butter, red meats and meat dishes, gravy, potatoes and potato dishes, vegetables, and sweets/desserts; - ‘Low Butter’: Higher in unsaturated fat spreads and oils; Diet based on macronutrient distribution, % energy from carbohydrate (C), fat (F), protein (P):; - ‘Low Red Meat’: 47% C, 37% F, 16% P; - ‘Traditional British’: 46% C, 39% F, 15% P; - ‘Low Butter’: 48% C, 35% F, 17% P; Dietary assessment methods: 24-h multiple pass dietary recall at baseline, ≥85y; Outcome assessment methods: Sarcopenia was defined using the European Working Group on Sarcopenia in Older Adults (EWGSOP) criteria:; - Low skeletal muscle index (<8.87 kg/m2 in men, <6.67 kg/m2 in women; via bioimpedance analysis); and; - Slow gait speed (≤0.8 m/s, via TUG test), and/or; - Weak grip strength (<16 kg in women, <26 kg in men; via dynamometer while standing). | [underlined: Significant]:; ‘Traditional Britis’ vs. ‘Low Butter’ pattern at age ≥85y and prevalent sarcopenia at 3y f/u: OR: 2.42, 95% CI: 1.15, 5.09, p=0.02.; When stratified by protein intake >1 or <1g/kg aBW/d, results were only significant in those with protein intake ≥1.0 g/kg BW/d: OR: 3.62, 95%CI: 1.33, 9.88, p=0.01; [underlined: Non-significant]:; ‘Low Red Meat’ vs. ‘Low Butter’’ pattern at age ≥85y and prevalent sarcopenia at 3y f/u, n=356: OR: 1.77, 95%CI: 0.84, 3.74, p=0.13, NS; ‘Low Red Meat’ vs. ‘Low Butter’’ pattern at age ≥85y and incident sarcopenia at 3y f/u, n=288: OR: 1.05, 95%CI: 0.37, 3.03, p=0.92, NS.; ‘Traditional British’ vs. ‘Low Butter’ pattern at age ≥85y and incident sarcopenia at 3y f/u, n=288: OR: 1.67, 95%CI: 0.59, 4.67, p=0.33, NS; Results were similar when stratified by protein intake >1 or <1g/kg aBW/d. | Key confounders accounted for:; Sex; SES; Anthropometry; Physical activity; Dietary protein intake; Other: Food energy; Depression; Cognitive status; Total number of chronic diseases; Total number of medications; Limitations:; - Did not account for the following key confounders: Age; Race/ethnicity; Physical disability; - Exposure occurred prior to start of f/u; - Only assessed dietary intake once at baseline; did not account for possible changes in dietary intake over f/u; - Did not account for missing data; - No published protocol; potential for selective outcome reporting; Funding Sources:; European Horizon 2020 PROMISS Project; National Institute for Health Research Newcastle Biomedical Research Centre; Tyne Hospitals NHS Foundation Trust; Newcastle University; UK Medical Research Council; Biotechnology and Biological Sciences Research Council; Dunhill Medical Trust; the Medical Council Research grant; NHS North of Tyne; Summary: Adherence to a ‘Traditional British’ compared to a ‘Low Butter’ dietary pattern at >85y was associated with higher risk of prevalent sarcopenia at 3y f/u. However, it was not significantly associated with incident sarcopenia.; Adherence to a ‘Low Red Meat’ compared to a ‘Low Butter’ dietary pattern was not significantly associated with risk of prevelant or incident sarcopenia.
Isanejad, 2018 ^3^; PCS, Osteoporosis Risk Factor and Prevention-Fracture Prevention Study (OSTPRE), Finland; Analytic N: 554 (Attrition: 26%); Age: 67.8y [1.85]; Sex: 100% female; SES: Income of 883.3 euros/mo [311.1]; Anthropometry: BMI of 26.5 kg/m^2^ [3.6] Total energy intake: 6576.5 kJ/d [1541]; Dietary protein intake: 67.85 g/d [18.0]; Physical activity: 47.5 h/mo [46.4]; - Physical disability: falls in past 12mo 21.8% | Dietary patterns:; Adherence to 2 dietary patterns was examined:; - Baltic Sea Diet Score (BSD)^vi^; ○ Positive components: Total fruits (mostly apples, pears) and berries, vegetables (root vegetables, legumes, nuts, mushrooms, and vegetable products, and excluding potatoes), fiber from cereal products, fish, low-fat milk, PUFA: SFA ratio; ○ Negative components: Processed meat products, total fat intake, alcohol; - Mediterranean Diet Score (MDS)^vii^; ○ Positive components: Total fruits (mostly apples, pears) and berries, vegetables (root vegetables, legumes and nuts, mushrooms, and vegetable products), cereals and potatoes, fish, PUFA+MUFA:SFA ratio; ○ Negative components: Meat (including sausage, eggs), milk and dairy products; ○ Moderation component: Alcohol; Diet based on macronutrient distribution: Total energy intake, and macronutrients/alcohol in g/d by quartiles of dietary patterns scores are reported in Table 2, 3 of article:; BSD scores; - Q1: 47.7% C, 34.9% F, 15.9% P; - Q2: 48.3% C, 32.1% F, 16.7% P; - Q3: 49.9% C, 41.1% F, 13.1% P; - Q4: 50.8% C, 27.1% F, 18.5% P; MDS scores; - Q1: 48.4% C, 31.7% F, 17.5% P; - Q2: 49.1% C, 30.8% F, 17.8% P; - Q3: 49.7% C, 31.1% F, 17.2% P; - Q4: 51.4% C, 29.9% F, 17.1% P; Dietary assessment methods: 3-d food record at baseline, age 68y; Outcome assessment methods: Sarcopenia was defined using EWGSOP criteria:; - Relative skeletal muscle index (RSMI) (lowest quartile, via DXA), and,; - Handgrip strength (any quartile, via dynamometer of dominant hand taken while sitting), and/or; - Walking speed (any quartile, time of 10m walk) | [underlined: Significant:]; BSD scores at 68y and sarcopenia after 3y f/u:; - Q1: OR: 1.00; - Q2: OR: 0.82, 95%CI: 0.30, 2.24; - Q3: OR: 0.76, 95%CI: 0.27, 2.13; - Q4: OR: 0.33, 95%CI: 0.13, 0.79; - p=0.015; [underlined: Non-Significant]:; BSD scores (continuous) at 68y and sarcopenia after 3y f/u: OR: −0.03 (0.01), p=0.512; MDS scores (continuous) at 68y and sarcopenia after 3y f/u: OR: −0.03 (0.02), p=0.67; MDS scores at 68y and sarcopenia after 3y f/u:; - Q1: OR: 1.00; - Q2: OR: 0.87, 95%CI: 0.33, 2.25; - Q3: OR: 1.20, 95%CI: 0.44, 3.23; - Q4: OR: 0.75, 95%CI: 0.28, 2.05 p=0.751 | Key confounders accounted for:; Sex; Age; SES; Anthropometry; Physical activity; Physical disability; Other: Energy intake, Smoking, Hormone Therapy, Osteoporosis, Rheumatoid Arthritis, Coronary Heart Disease, Depression, Diabetes; Limitations:; - Did not account for the following key confounders: Race/ethnicity; Dietary protein intake; - Subjects volunteered for a study on falls/fracture prevention; exposure occurred prior to start of f/u; - Only assessed dietary intake once at baseline; did not account for possible changes in dietary intake over f/u; - Did not account for missing data; - Combined pre-sarcopenic and sarcopenic women; - No published protocol; likely selective outcome reporting; Funding Sources:; The Finnish Cultural Foundation, Sigrid Juselius Foundation, Academy of Finland, Kuopio University Hospital, Päivikki and Sakari Sohlberg Foundation, Finnish Cultural Foundation, North Savo Regional Fund, Otto. A Malm Foundation, Yrjö Jahnsson Foundation, Juho Vainio Foundation; Summary: Higher BSD score (categorical) at 68y was significantly associated with reduced risk of sarcopenia after 3y f/u. However, associations were not significant when BSD was analzyed continuously.; MDS score at 68y was not signicantly associated with risk of sarcopenia after 3y f/u.
Karlsson, 2019 ^4^; PCS, Uppsala Longitudinal Study of Adult Men (ULSAM), Sweden; Analytic N: 254 (Attrition: 78%); Age: 70.9y, [0.6]; Sex: 0% female; SES: 48% 6-7y education, 48% high school education, 31% university educationow education; Anthropometry: BMI of 25.9 kg/m^2^ [2.9]; Dietary protein intake: 42% <0.8g/kg, 34% 0.8-1.0 g/kg, 25% >1.0 g/kg; Physical activity: 68% regular | Dietary patterns:; Adherence to 2 dietary patterns was examined:; - Modified Healthy Diet Indicator (mHDI); ○ Positive components: PUFA, protein, carbohydrates, fiber, fruit and vegetables, fish; ○ Negative components: Sucrose, SFA, cholesterol; - Modified Mediterranean Diet Score (mMDS); ○ Positive components: PUFA:SFA ratio, vegetables and legumes, fruit and berries, cereals and potatoes, fish; ○ Negative components: Meat and meat products, milk and milk products; ○ Moderation component: Alcohol; Dietary assessment methods: 7-d weighed food record at baseline, age 71y; Outcome assessment methods: Sarcopenia was defined using EWGSOP criteria:; - Low muscle mass (skeletal muscle mass index <7.26 kg/m; via DXA); - Low handgrip strength (<30 kg; via dynamometer of dominant hand taken while sitting); - Low muscle performance (gait speed <0.8m/s; via intermediate 6m of a 10m walk) | [underlined: Significant:]; mHDI score (medium vs. low) at 71y and sarcopenia at 87y: OR: 0.38, 95% CI: 0.15, 0.97; mMDS score (continuous) at 71y and sarcopenia at age 87y: OR: 0.49, 95% CI: 0.31, 0.80; [underlined: Non-Significant:]; mHDI score (high vs. low) at 71y and sarcopenia at 87y: OR: 0.47, 95% CI: 0.17, 1.28, p=NS; mHDI scores (continuous) at 71y and sarcopenia at 87y: OR: 0.90, 95% CI: 0.63, 1.27, p=NS; mMDS score (high vs. low; medium vs. low) at 71y and sarcopenia at 87y: OR: 0.33, 95% CI: 0.09, 1.23, p=NS; OR: 0.50, 95% CI: 0.22, 1.16, p=NS | Key confounders accounted for:; Sex; Age; SES; Anthropometry; Dietary protein intake; Physical activity; Other: Smoking; Inflammation (CRP); Hospital stay; Limitations:; - Did not account for the following key confounders: Race/ethnicity; Physical disability; - Excluded subjects with >10% weight loss between 60-70y; exposure occurred prior to start of f/u; - Only assessed dietary intake once at baseline, and document instability in dietary intake over the course of the study; were not able to not account for possible changes in dietary intake over f/u; - Did not account for missing data; - No published protocol; potential for selective outcome reporting; Funding Sources:; Swedish Medical Research Council, Uppsala University; Summary: Higher mHDI score (medium vs. low) at 71y was significantly associaeted with lower risk of sarcopenia at 87y. However, high vs. low score and analysis of scores continuously were not significantly associated with risk of sarcopenia.; Higher mMDS score (continuous) at 71y was associated with lower risk of sarcopenia at 87y. However, when mMDS scores were analyzed categorically (low vs. medium or high), there were no significantly associations with risk of sarcopenia.

Table 2 Summary of the results from studies that examined the relationship between dietary patterns and diets based on macronutrient distribution and sarcopenia^viii^

Article, Study Design, Country | Dietary Patterns | Significant Results | Non-Signigicant Results
Chan, 2016 ^1^; PCS; Hong Kong, China | Dietary Quality Index-International score (DQI-I); - Positive components: Vegetables, fruit, grain, fiber, protein, iron, calcium, vitamin C, overall food group variety, within food group variety; - Moderation components: Total fat, SFA, cholesterol, sodiu, empty calorie foods, macronutrient ratio, fatty acid ratio | | Men: OR: 1.00, 95% CI: 0.98, 1.02, p=0.670, NS; Women: OR: 0.99, CI: 0.97, 1.02, p=0.611, NS
| Mediterranean Diet Score (MDS); - Positive components: Vegetables, legumes, fruit and nuts, cereals, fish, MUFA:SFA ratio; - Negative components: Red and processed meat, dairy products; - Moderation components: Alcohol | | Men: OR: 0.98, 95% CI: 0.86, 1.10, P=0.678, NS; Women: OR: 0.96, CI: 0.83, 1.11, p=0.602, NS
| “Vegetables-Fruits”: Higher in tomatoes, dark green and leafy vegetables, cruciferous vegetables, starchy vegetables, other vegetables, soy, fruits, legumes, mushroom and fungi, and lower in fats and oils | | Men: OR: 1.07, 95% CI: 0.88, 1.29, p=0.522, NS; Women: OR: 1.15, CI: 0.94, 1.40, p=0.190, NS
| “Snacks-Drinks-Milk Products”: Higher in condiments, coffee, fast food, nuts, French fries and potato chips, milk and milk products, whole grains, sweets and desserts, beverage | | Men: OR: 0.95, CI: 0.78, 1.16, p=0.611, NS; Women: OR: 1.20, CI: 0.94, 1.53, p=0.148, NS
| “Meat-Fish”: Higher in dim sum, red and processed meats, poultry, fish and seafood, wine , and lower in refined grains | | Men: OR: 1.00, 95% CI: 0.84, 1.20, p=1.000, NS; Women: OR: 1.10, CI: 0.87, 1.40, p=0.415, NS
Granic, 2019 ^2^; PCS; United Kingdom | - ‘Low Red Meat’: lower in legumes, sweets and desserts, and higher in fish/seafood; macronutrient distribution: 47% C, 37% F, 16% P; - ‘Traditional British’: higher in butter, red meats and meat dishes, gravy, potatoes and potato dishes, vegetables, and sweets/desserts; macronutrient distribution: 46% C, 39% F,15% P; - ‘Low Butter’: Higher in unsaturated fat spreads and oils; macronutrient distribution: 48% C, 35% F, 17% P | ‘Traditional British’ vs. ‘Low Butter’: OR: 2.42, 95% CI: 1.15, 5.09, p=0.02.; Protein intake ≥1.0 g/kg BW/d: OR: 3.62, 95%CI: 1.33, 9.88, p=0.01 | ‘Low Red Meat’ vs. ‘Low Butter’’: OR: 1.77, 95%CI: 0.84, 3.74, p=0.13, NS; ‘Low Red Meat’ vs. ‘Low Butter’’: OR: 1.05, 95%CI: 0.37, 3.03, p=0.92, NS.; ‘Traditional British’ vs. ‘Low Butter’: OR: 1.67, 95%CI: 0.59, 4.67, p=0.33, NS
Isanejad, 2018 ^3^; PCS; Finland | Baltic Sea Diet Score (BSD); - Positive components: Total fruits (mostly apples, pears) and berries, vegetables (root vegetables, legumes, nuts, mushrooms, and vegetable products, and excluding potatoes), fiber from cereal products, fish, low-fat milk, PUFA: SFA ratio; - Negative components: Processed meat products, total fat intake, alcohol; - Macronutrient distribution of % energy for BSD quartiles:; ○ Q1: 47.7% C, 34.9% F, 15.9% P; ○ Q2: 48.3% C, 32.1% F, 16.7% P; ○ Q3: 49.9% C, 41.1% F, 13.1% P; ○ Q4: 50.8% C, 27.1% F, 18.5% P | - Q1: OR: 1.00; - Q2: OR: 0.82, 95%CI: 0.30, 2.24; - Q3: OR: 0.76, 95%CI: 0.27, 2.13; - Q4: OR: 0.33, 95%CI: 0.13, 0.79; - p=0.015 | Continuous: OR: −0.03 (0.01), p=0.512
| Mediterranean Diet Score (MDS); - Positive components: Total fruits (mostly apples, pears) and berries, vegetables (root vegetables, legumes and nuts, mushrooms, and vegetable products), cereals and potatoes, fish, PUFA+MUFA:SFA ratio; - Negative components: Meat (including sausage, eggs), milk and dairy products; - Moderation component: Alcohol; - Macronutrient distribution of % energy for MDS quartiles:; ○ Q1: 48.4% C, 31.7% F, 17.5% P; ○ Q2: 49.1% C, 30.8% F, 17.8% P; ○ Q3: 49.7% C, 31.1% F, 17.2% P; ○ Q4: 51.4% C, 29.9% F, 17.1% P | | - Q1: OR: 1.00; - Q2: OR: 0.87, 95%CI: 0.33, 2.25; - Q3: OR: 1.20, 95%CI: 0.44, 3.23; - Q4: OR: 0.75, 95%CI: 0.28, 2.05; - p=0.751; Continuous: OR: −0.03 (0.02), p=0.67
Karlsson, 2019 ^4^; PCS; Sweden | Modified Healthy Diet Indicator (mHDI); - Positive components: PUFA, protein, carbohydrates, fiber, fruit and vegetables, fish; - Negative components: Sucrose, SFA, cholesterol | Medium vs. Low: OR: 0.38, 95% CI: 0.15, 0.97 | High vs. Low: OR: 0.47, 95% CI: 0.17, 1.28, p=NS; Continuous: OR: 0.90, 95% CI: 0.63, 1.27, p=NS
| Modified Mediterranean Diet Score (mMDS); - Positive components: PUFA:SFA ratio, vegetables and legumes, fruit and berries, cereals and potatoes, fish; - Negative components: Meat and meat products, milk and milk products; - Moderation component: Alcohol | Continuous: OR: 0.49, 95% CI: 0.31, 0.80 | Medium vs. Low: OR: 0.33, 95% CI: 0.09, 1.23, p=NS; High vs. Low: OR: 0.50, 95% CI: 0.22, 1.16, p=NS

Table 3 Risk of bias for observational studies examining dietary patterns and diets based on macronutrient distribution and sarcopenia^ix,^ ^x^

Article | Confounding | Selection of participants | Classification of exposures | Deviations from intended exposures | Missing data | Outcome measurement | Selection of the reported result
Chan, 2016 ^1^ | Serious | Serious | Low | Serious | Moderate | Low | Moderate
Granic, 2019 ^2^ | Serious | Moderate | Low | Serious | Moderate | Low | Moderate
Isanejad, 2018 ^3^ | Serious | Serious | Low | Serious | Moderate | Moderate | Serious
Karlsson, 2019 ^4^ | Serious | Moderate | Low | Critical | Serious | Low | Moderate

ii A detailed description of the methodology used for grading the strength of the evidence is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

iii Abbreviations: AMDR, Acceptable macronutrient distribution range; C, dietary carbohydrate; CI, confidence interval; CRP, c-reactive protein; DQI-I, Diet quality index - international; DXA, dual-energy X-ray absorptiometry; EWGSOP, European Working Group on Sarcopenia in Older People; F, dietary fat; f/u, Follow-up; mHDI, modified Healthy Diet Indicator; MDS, Mediterranean diet score; NS, not significant; OR, odds ratio; P, dietary protein; PCS, Prospective cohort study design; PRO, Protein; Q, Quantile (quintile or quartile as appropriate); RR, Relative risk; SES, Socioeconomic status; y, years

iv Kim S, Haines PS, Siega-Riz AM, Popkin BM. The Diet Quality Index-International (DQI-I) provides an effective tool for cross-national comparison of diet quality as illustrated by China and the United States. J Nutr 2003;133: 3476e3484.14608061

v Trichopoulou A, Costacou T, Bamia C, Trichopoulos D. Adherence to a Mediterranean diet and survival in a Greek population. N Engl J Med 2003;348: 2599e2608.12826634

vi Kanerva N, Kaartinen NE, Schwab U, Lahti-Koski M, Männistö S (2014) The Baltic Sea Diet Score: a tool for assessing healthy eating in Nordic countries. PHN 17(8):1697–1705 24172174

vii Sofi F, Macchi C, Abbate R, Gensini GF, Casini A (2014) Mediterranean diet and health status: an updated meta-analysis and a proposal for a literature-based adherence score. PHN 17(12):2769–2782.24476641 ; Tognon G, Rothenberg E, Eiben G, Sundh V, Winkvist A,Lissner L (2011) Does the Mediterranean diet predict longevity in the elderly? A Swedish perspective. Age 33(3):439–450.21110231 ; Bamia C, Lagiou P, Buckland G, Grioni S, Agnoli C, Taylor AJ (2013) Mediterranean diet and colorectal cancer risk: results from a European cohort. Eur J Epidemiol 28(4):317–328.23579425

viii Abbreviations: AMDR, Acceptable macronutrient distribution range; C, Carbohydrate; DQI-I, Diet quality index - international; EWGSOP, European Working Group on Sarcopenia in Older Adults; F, fat; f/u, Follow-up; MDS, Mediterranean diet score; NS, not significant; OR, odds ratio; PCS, Prospective cohort study design; P, Protein; Q, Quantile (quintile or quartile as appropriate); RR, Relative risk; SES, Socioeconomic status

ix A detailed description of the methodology used for assessing risk of bias is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

x Possible ratings of low, moderate, serious, critical, or no information determined using the “Risk of Bias for Nutrition Observational Studies” tool (RoB-NObs) ( Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC. )